# APPENDIX G SUBSTANCE USE DISORDER OUTCOMES CATEGORIZATION

Author, Year, PMID | Study Outcome Definition | Categorization for Report
Chang, 2014, 25158998 | Substance Abuse [Hospital visits or deaths with ICD-10 codes: F11–F16, F19; deaths, and convictions for a substance-related crime] | SUD
Steinhausen, 2014, 24314850 | Substance Use Disorder [ICD-8: 303, 304; ICD-10: F1] | SUD
Dalsgaard, 2014, 24090624 | Substance Use Disorder [Psychiatric admissions in adulthood due to substance use disorder (ICD-8 or ICD-10: 304 or F 11.x–19.x)] | SUD
Mannuzza, 2008, 18381904 | Substance Use Disorder [DSM-III-R substance use disorder diagnosed in late adolescence or young adulthood] | SUD
Torgersen, 2013, 23104523 | Substance Use Disorder [DSM-IV; alcohol, amphetamines, cannabis and opiates] | SUD
Wilens, 2006, 16601645 | Substance Use Disorder [DSM-IV] | SUD
Biederman, 2008, 18316421 | Alcohol Abuse Disorder [DSM-IV] | AUD
Biederman, 2008, 18316421 | Alcohol Dependence Disorder [DSM-IV] | AUD
Dalsgaard, 2014, 24090624 | Alcohol Abuse Disorder / Alcohol Dependence [Psychiatric admissions in adulthood due to alcohol use disorder or alcohol dependence (ICD-8 or ICD-10: 291, 303 or F 10.x)] | AUD
Mannuzza, 2008, 18381904 | Alcohol Use Disorder [DSM-III-R] | AUD
Biederman, 2008, 18316421 | Drug Abuse Disorder [DSM-IV] | Non-alcohol substance use disorders or stimulant use disorders
Biederman, 2008, 18316421 | Drug Dependence Disorder [DSM-IV] | Non-alcohol substance use disorders or stimulant use disorders
Mannuzza, 2008, 18381904 | Non-Alcohol Substance Use Disorder [DSM-III-R] | Non-alcohol substance use disorders or stimulant use disorders
Mannuzza, 2008, 18381904 | Stimulant Use Disorder [DSM-III-R] | Non-alcohol substance use disorders or stimulant use disorders