# APPENDIX F STUDY INTERVENTIONS

Study, Year, PMID, Study Design, Trial Registration Number | Arms | Description of Arms | Length of Treatment, Mean (SD) | Length of Follow-Up | Attrition Rate
Key Question 1
Biederman, 2008^a^, 18316421, NRCS (P) | Lifetime stimulant therapy | Subjects reported a lifetime history of treatment with any stimulant (amphetamine products, methylphenidate products, and pemoline)^b^ and did not meet criteria for the substance use outcome before the onset of treatment. | 6 (4.7) years | 10 years | 20% (N=28) lost to follow-up
Biederman, 2008^a^, 18316421, NRCS (P) | No stimulant therapy | Untreated subjects and subjects who began stimulant treatment after the onset of the substance use. | NR
Wilens, 2006^a,c^, 16601645 Single Group (P) | ADHD medication | Stimulants (96%)^d^ | NR | 10 years | NR
Chang, 2014, 25158998, NRCS (R) | Stimulant ADHD medication | Use of Methylphenidate (N06BA04), amphetamine (N06BA01), dexamphetamine (N06BA02) on January 1, 2006. | NR | 3 years | NR
Chang, 2014, 25158998, NRCS (R) | No stimulant ADHD medication | Non-stimulant ADHD medication or unmedicated on January 1, 2006. | NR
Dalsgaard, 2014, 24090624, Single Group (P) | Stimulant medication | Methylphenidate or dexamphetamine in childhood | NR | NR | NR
Mannuzza, 2008, 18381904, Single group (P) | ADHD group | Methylphenidate; 41.7mg (SD=12.4) daily | 23.2 (18.6) months | Estimated 13-19 years^e^ | 15% loss (85% retention at adult assessment)
Steinhausen, 2014, 24314850, NRCS (R) | Methylphenidate | Methylphenidate (NA06BA04 and NA06BA11) | 2.69 (3.04)^f^ years | Estimated 14 years | NR
Steinhausen, 2014, 24314850, NRCS (R) | Mixed Medication | Methylphenidate (83.51%), antidepressants (62.69%), antipsychotics (59.45%), other ADHD-specific drugs (32.74%), and amphetamines (3.40%) | 5.19 (6.36)^f^ years | Estimated 14 years | NR
Steinhausen, 2014, 24314850, NRCS (R) | No medication | N/A | N/A | Estimated 14 years | NR
Torgersen, 2013, 23104523, Single Group (R) | ADHD with No comorbid SUD | Methylphenidate; maximum dose 58.7 (23.3), maintenance dose 60 (22.8) | 41.4 (30.4) months | Minimum of 43 months | NR
Key Question 2
Kast, 2021, 33988929, NRCS (R) | Stimulant group | Those receiving stimulants within 90 days of admission^g^ | Estimated 2 years^h^ | 5.5-years | NR
Kast, 2021, 33988929, NRCS (R) | Non-Stimulant | Those receiving non-stimulants within 90 days of admission. | Estimated 2 years^h^ | 5.5-years | NR
Kast, 2021, 33988929, NRCS (R) | No medication | No Treatment | NR | 5.5-years | NR
Konstenius, 2010, 20015599, RCT, ISRCTN 81602628 | Methylphenidate | Extended-release methylphenidate; starting dose (18 mg) of methylphenidate which was titrated over period of 10 days to the maximum dose of 72 mg. All subjects participated once weekly in an individual skills training program which targeted risk for relapse in drug use and ADHD symptoms. | 12 weeks^i^ | 12 weeks^i^ | NR
Konstenius, 2010, 20015599, RCT, ISRCTN 81602628 | Placebo | Placebo. All subjects participated once weekly in an individual skills training program which targeted risk for relapse in drug use and ADHD symptoms. | 12 weeks^i^ | 12 weeks^i^ | NR
Levin, 2006, 16102908, RCT | Methylphenidate | Sustained-release methylphenidate (two capsules and two tablets twice per day); Started at 10 mg/day and increased by 10 mg/day, up to 40 mg/day. The standard formula then replaced the Sustained-release formulation and dose was increased to maximal dose of 80 mg/day. Patients who could not tolerate at least 40 mg/day of methylphenidate were discontinued. All participants attended weekly individual CBT. | 10 weeks^j^ | 10 weeks^j^ | None (ITT analysis); 11 (34.4%) did not completed the treatment period
Levin, 2006, 16102908, RCT | Bupropion | Sustained release bupropion (two capsules and two tablets twice per day); Started at 100 mg/day and increased by 100 mg by the end of the first week and increased to a maximum dose of 400 mg/day in the second week. Patients who could not tolerate a dose of at least 200 mg/day of bupropion were discontinued. All participants attended weekly individual CBT. | 10 weeks^j^ | 10 weeks^j^ | None (ITT analysis); 10 (30.3%) did not completed the treatment period
Levin, 2006, 16102908, RCT | Placebo | Placebo (2 capsules and 2 tablets twice per day); 1 mg tablet of folic acid Also, after 49 randomized patients, 100 mg/day of riboflavin was added to all capsules to track compliance. All participants attended weekly individual CBT. | 10 weeks^j^ | 10 weeks^j^ | None (ITT analysis); 8 (24.2%) did not completed the treatment period
Levin, 2007, 16930863, RCT | Methylphenidate | Methylphenidate 2 times/day (2 capsules twice a day) and CBT 1/week; dosing initiated at 10 mg/day of standard formulation methylphenidate and increased up to 20 mg two times a day (40 mg/day). If tolerated, sustained-released formulation replaced the standard formula and used at either 20 mg 2 times a day or 60mg/day (20mg 1/day and 40mg 1/day). Patients who could not tolerate a dose of at least 40 mg/day of methylphenidate were discontinued off the medication but were continued in the trial. | 13 Weeks^k^ | 13 Weeks^k^ | None (ITT analysis); 30 (56.6%) did not completed the treatment period
Levin, 2007, 16930863, RCT | Placebo | Placebo 2 times/day (2 capsules twice a day) and CBT 1/week; Folic acid in the form of a 1 mg tablet and 25 mg of riboflavin was added to each of the four prescribed capsules (approximately 100 mg/day) to track compliance. | 13 Weeks^k^ | 13 Weeks^k^ | None (ITT analysis); 29 (54.7%) did not completed the treatment period
Levin, 2015^l^, 25887096, RCT, NCT00553319 | 60mg mixed amphetamine salts | 60-mg/day extended-release mixed amphetamine salts in 100 mg of riboflavin tablet; plus CBT 1/week. Participants unable to tolerate the maximum doses had their doses reduced based on clinical assessment. | 13 weeks^m^ | 13 weeks^m^ | None (ITT analysis); 10 (25%) did not completed the treatment period
Levin, 2015^l^, 25887096, RCT, NCT00553319 | Placebo | Placebo in 100 mg of riboflavin tablet; plus CBT 1/week | 13 weeks^m^ | 13 weeks^m^ | None (ITT analysis); 14 (32.6%) did not completed the treatment period
Notzon, 2016^l^, 28051838, RCT | Extended-release mixed amphetamine salt | Extended-release mixed amphetamine salts; 60 or 80 mg daily. Weekly CBT addressing cocaine use. | 13 weeks^m^ | NR | NR
Notzon, 2016^l^, 28051838, RCT | Placebo | Weekly CBT addressing cocaine use. | 13 weeks^m^ | NR | NR
Schubiner, 2002, 12233989, RCT | Methylphenidate | The doses were titrated from an initial dosage for the first 2 or 3 days (10 mg three times a day) to a second-level dosage (20 mg three times a day) for the next 4 to 5 days and finally to the target dosage of 30 mg three times a day by Day 8. All participants received twice-weekly CBT for cocaine dependence and weekly CBT for ADHD. | 12 weeks^n^ | 12 weeks^n^ | 55% did not complete the study
Schubiner, 2002, 12233989, RCT | Placebo | All participants received twice-weekly CBT for cocaine dependence and weekly CBT for ADHD. | 12 weeks^n^ | 12 weeks^n^ | 42% did not complete the study

Notes.

a Copublication;

b Amphetamine products included mixed amphetamine salts, D-amphetamine; methylphenidate products included immediate-release methylphenidate, osmotic-release oral system methylphenidate, transdermal methylphenidate, d-methylphenidate, extended-release methylphenidate;

c 64% of subjects in this study were probands from Biederman, 2008 who were taking medications;

d Other medications included selective serotonin reuptake inhibitors (31%), tricyclic antidepressants (21%), a-adrenergic agents (15%), neuroleptics (6%), and benzodiazepines (4%);

e Based on age at baseline and average follow-up time for adult assessment;

f Based on full study sample;

g 67% were extended release or prodrug formulations;

h Based on figure provided;

i Trial duration was 13 weeks, which included baseline measurements and 12 weeks of treatment;

j Trial was 12 weeks and included a 2-week placebo lead-in phase, a 2-week dose titration period, followed by 8 weeks at a stable dose;

k 1-week placebo lead-in phase, a 2-week dose titration phase followed by 11 weeks at a stable dose;

l Copublication;

m A placebo lead-in period [week 1] preceded randomization followed by a 13-week trial with dose titrated in the first week and tapered down in the last week;

n Included 1 week of baseline testing and 12 weeks of treatment.

Abbreviations. ADHD=attention-deficit/hyperactivity disorder; CBT=cognitive behavioral therapy; ITT=intention to treat; mg=milligram; N/A=not applicable; N=number; NR=not reported; NRCS=non-randomized comparative study; P=prospective; PMID=PubMedID; R=retrospective; SD=standard deviation.