# APPENDIX E BASELINE CHARACTERISTICS

Author Year PMID, Study Design | N at Baseline | Race/Ethnicity, % | Age at Baseline (Years), Mean (SD) | Age at Treatment Initiation (Years), Mean (SD) | Male, % | Comorbidities, %/Mean (SD) | Socioeconomic Status Details, %/Mean (SD)
Key Question 1
Biederman, 2008, 18316421, NRCS (P) | 131 | White 100 | 10.5 (2.9)^a,b^ | 8.8 (3.5)^b^ | 100 | Conduct disorder, 45.8^b,c^ | Hollingshead Scale, 1.86 (1.0)^b^
Wilens, 2006, 16601645, Single group (P) | 55^d,e^ | White 100 | Range: 6-17 | NR | 82 | NR | Hollingshead scale: 2 (1)
Chang. 2014, 25158998, NRCS (R) | 38,753 | NR | 8-15= 44.5%; 16-25= 30.7%; 25-35= 13.3%; 36-46= 11.4% | NR | 68 | Nonsubstance psychiatric diagnosis, 60.7 | Employed, 24; Living in a metropolitan area, 14
Dalsgaard, 2014, 24090624, Single group (P) | 208 | NR | NR | NR | 88 | NR | NR
Mannuzza, 2008, 18381904, Single group (P) | 176 | White 100 | 6-12 | 8.7 (1.6); Range: 6-12 | 100 | NR | Hollingshead and Redlich index, 3.3 (1.0)^b^
Steinhausen, 2014, 24314850, NRCS (R) | 18,702^f^ | NR | 15.20 (10.08)^g^ | NR | 75.4^g^ | NR | NR
Torgersen, 2013, 23104523, Single group (R) | 52^h^ | NR | 28.4 (8.2) | NR | 65.4 | Comorbid antisocial personality disorder, 1.9; Comorbid borderline personality disorder, 13.5 | NR
Key Question 2
Kast, 2021, 33988929, NRCS (R) | 203 | White 89.6 | 38.0 (11.0)^b^ | NR | 57.6 | Cocaine use disorder, 30.5 | NR
Konstenius, 2010, 20015599, RCT | 24 | NR | 37.4 (9.9)^b^ | NR | 75 | NR | Means of livelihood:; Employed, 20.8; Social welfare, 70.8; Unspecified, 8.3
Levin, 2006, 16102908, RCT | 98 | White 39.8; Hispanic 39.8; Black 20.4 | 39.0 (7.4)^b^ | NR | 57 | Current substance use disorders; Alcohol, 17.3; Marijuana, 18.4; Cocaine, 53.1; Opiate, 53.1; Psychiatric disorders; Current:; Affective, 17.3; Anxiety, 17.3; Lifetime:; Affective, 26.5; Anxiety, 12.2 | Education (years), 12 (3) ^b^; Currently employed, 57.1; Average income, $20,574 ($14525)^b^
Levin, 2007, 16930863, RCT | 106 | White 60.4; Hispanic 14.2; African American 19.8; Others 5.7 | 37 (23-52)^b^; Mean (range) | NR | 83 | Current substance use disorders:; Alcohol, 40.6; Marijuana, 40; Opiate, 0.9; Psychiatric disorders:; Lifetime anxiety/affective, 19.8; Current anxiety/affective, 45.3 | Employment:; Full-time, 56.6; Part-time, 18.9; Unemployed, 16; Income:; <25k, 34; 25–50k, 37.7; >50k, 16
Levin, 2015, 25887096, RCT | 126 | White 57.1; Hispanic 20.6; Black 17.5; Asian 7.9 | 40.4 (8.1)^b^ | NR | 84.1 | Alcohol dependence:; Current, 22.2; Lifetime, 51.6; Cannabis dependence:; Current, 10.3; Lifetime, 30.2 | Current employment:; Full-time, 32.5; Part-time, 10.3; Unemployed, 54.8
Notzon, 2016, 28051838, RCT | 57^i^ | White 64.9; Hispanic 10.5; Black 17.5; Asian 1.8 | 38.3 (8.0)^b^ | NR | 78.9 | NR | Education (years), 14.1 (2.20)
Schubiner, 2002, 12233989, RCT | 48 | White 62.5 | 37.1 (6.7)^b^ | NR | 89.6 | BDI scores, 22.5 (9.0)^b^; Addiction Severity Index (psychiatric status), 0.3 (0.2)^b^; Any Axis I comorbidity^j^ 56.3 | NR

Notes. Co-publications are Biederman-2008 and Wilens-2006, Levin-2015 and Notzon-2016.

a Samples restricted to subjects who were assessed at the 10-year follow-up (no stimulant treatment history, N = 30 and stimulant therapy subjects, N = 82);

b Calculated by the research team;

c Patients with lifetime history of conduct disorder (status at baseline);

d Data represents ADHD group;

e 64% of subjects in this study were probands from the Biederman, 2008;

f Data include all individuals in the methylphenidate, mixed medication, and no treatment groups less those with SUD prior to onset of medication;

g Data represents estimates from full population included in the study (N = 20,742);

h No comorbid substance use disorder group only;

i Only included those with marijuana outcomes analyses from the Levin 2015 study;

j Axis I comorbidity data represents Affective, Anxiety and Other Axis I disorders.

Abbreviations. BDI=Beck Depression Inventory, NR=not reported, NRCS=non-randomized comparative studies, P=prospective, R=retrospective.