# APPENDIX D DESIGN DETAILS

Author Year; PMID; Protocol/Trial | Country; Setting; Funding | Study Design | Enrollment Dates | Inclusion Criteria | Exclusion Criteria | ADHD Definition | SUD Definition (KQ 2)
Key Question 1
Biederman 2008; 18316421 | USA; Outpatient; NR | NRCS (P) | NR | Individuals derived from longitudinal case-control study of ADHD. | Adopted; nuclear family was not available; major sensorimotor disabilities (paralysis, deafness, blindness); psychosis; autism, inadequate English language; IQ<80. | DSM-III-R | –
Wilens 2006; 16601645 | USA; Outpatient; Non-Industry | Single Group (P) | NR | Aged 6-17 years | Adoption; nuclear family is not available; sensorimotor handicaps; psychosis, autism, inadequate command of the English language; Full Scale IQ < 80 | DSM-III-R | –
Chang 2014; 25158998 | Sweden; Outpatient; Non-Industry | NRCS (R) | 2006-2009 | Born during 1960-1998 in Sweden; ≥1 outpatient ADHD diagnosis during 2001-2009 in the National Patient Register. | NR | ICD-10 code: F90 | –
Dalsgaard 2014; 24090624 | Denmark; Outpatient; Non-Industry | Single Group (P) | NR | Treated with methylphenidate or dexamphetamine in childhood. | NR | DSM-IV, ICD-10 | –
Mannuzza 2008; 18381904 | USA; Outpatient; Non-Industry | NRCS (P) | 1970-1977 | Referral to a psychiatric clinic for behavioral problems; elevated ratings on standard scales of hyperactivity by teachers and parents; behavior problems in settings other than school; a diagnosis of DSM-II hyperkinetic reaction by a child psychiatrist; IQ score >85, English speaking parents; home phone. | Prior treatment with stimulants; psychosis or neurological disorder; referrals that involved aggressive or other serious antisocial behaviors. | DSM-IV | –
Steinhausen 2014; 24314850 | Denmark; Community; NR | NRCS (R) | 1994-2010 | Diagnosed with ADHD between 1994 and 2010 in the Danish psychiatric central register (DPCR) | NR | ICD-8 or 10 | –
Torgersen 2013; 23104523 | Norway; Outpatient; NR | Single Group (R) | 1997-2005 | Adult ADHD diagnosis (≥18 years); initiated central stimulant treatment. | NR | ADHD confirmed by a regional expert committee for hyperkinetic disorders according to national guidelines | –
Key Question 2
Kast 2021; 33988929 | USA; Outpatient; Non-Industry | NRCS (R) | 2014-2020 | ADHD Diagnosis; referred or presenting newly to an addiction psychiatry clinic. | NR | DSM 5; ICD-10 code F90 | DSM 5
Konstenius 2010; 20015599; ISRCTN81602628 | Sweden; Community; Industry | RCT | NR | Treated at outpatient addiction units in the Stockholm metropolitan region; amphetamine dependence during the last 12 months. | Current or past diagnosis of any other substance dependence except nicotine; history of major psychiatric disorder or any current psychiatric condition requiring medication; use of opioid medication or illicit opiates in the last month; current use of benzodiazepines; traces of illicit substance in the urine; serious somatic disease; pregnant or lactating; known hypersensitivity for methylphenidate; IQ < 70 | Conners’ adult ADHD self and observer rating scales (CAARS:SV and CAARS:O) | DSM IV (amphetamine dependence)
Levin 2006; 16102908 | USA; Outpatient; Non-Industry | RCT | NR | DSM-IV criteria for opiate dependence and adult ADHD; aged 18-60; the same dose of methadone for at least 3 weeks. | Met DSM-IV criteria for current psychiatric disorders (other than ADHD/SUD); history of eating disorder; physiologically dependent on sedatives or alcohol; suicidal or homicidal behavior within the past 2 years; prescribed psychotropic medications other than methadone; unstable medical condition (i.e., uncontrolled diabetes); sensitivity to MPH or BPR; nursing and/or pregnant; unable to give informed consent | DSM-IV | DSM-IV (opiate dependence)
Levin 2007; 16930863 | USA; Outpatient; Non-Industry | RCT | 1998-2004 | Aged 18–60 years; cocaine dependence and seeking treatment for cocaine use; persistent adult ADHD. | Psychiatric disorders (other than ADHD or SUD) requiring psychiatric intervention; physiologically dependent on opioids, sedatives, or alcohol; suicidal or homicidal behavior within the past 2 years; current psychotropic medication; unstable medical condition (i.e. uncontrolled diabetes); known sensitivity to MPH; nursing and/or pregnant; unable to give consent. | DSM-IV | DSM-IV
Levin 2015; 25887096; NCT00553319 | USA; Community; Non-Industry | RCT | 2007-2013 | Current treatment for cocaine use disorder; aged 18-60 years, medically and psychiatrically stable, diagnosis of cocaine dependence and adult ADHD. | Past mania, schizophrenia, or any psychotic disorder other than transient psychosis due to drug abuse; uncontrolled hypertension or coronary vascular disease; cardiac symptoms, fainting, open-heart surgery, and/or arrhythmia; legally mandated to substance abuse treatment. | DSM-IV-TR | DSM-IV-TR
Notzon 2016; 28051838 | USA; Outpatient; NR | RCT | 2007-2013 | Aged 18–60; adult ADHD and current cocaine dependence; marijuana use in the 30 days prior to study enrollment. | History of mania, schizophrenia, or any psychosis beyond transient symptoms related to drug use; abnormal cardiac function; any unstable medical or psychiatric conditions | DSM IV | Conners; Adult ADHD Diagnostic Interview for DSM-IV and the SCID for DSM-IV
Schubiner 2002; 12233989 | USA; Outpatient; NR | RCT | 2002-NR | Aged 18-55 years; current cocaine dependence; provided urine specimen with a positive urine toxicology result for cocaine metabolite; ADHD in childhood and adulthood; willing to enter an intensive outpatient treatment program. | IQ < 75 on the Shipley Institute of Living scale | DSM IV | DSM–IV (cocaine dependence)

Abbreviations. ADHD=attention-deficit/hyperactivity disorder; DSM=Diagnostic and Statistical Manual of Mental Disorders; ICD=International Classification of Diseases; IQ=intelligence quotient score; KQ=key question; NR=not reported; NRCS=non-randomized comparative study; (P)=prospective; PMID=PubMed ID; (R)=retrospective; SCID=Structured Clinical Interview for DSM Disorders; SUD=substance use disorder.