# APPENDIX C RISK OF BIAS ASSESSMENTS

Author, Year, PMID, Design | Detection Bias (Blinding of Outcome Accessors) | Attrition Bias | Clear Reporting | Eligibility Criteria Clear | Intervention Adequately Described | Outcomes Fully Defined | RCT | | | | | NRCS & Single groups | NRCS | | Other Bias | Overall RoB
Author, Year, PMID, Design | Detection Bias (Blinding of Outcome Accessors) | Attrition Bias | Clear Reporting | Eligibility Criteria Clear | Intervention Adequately Described | Outcomes Fully Defined | Blinding of Participants and Personnel | Random Sequence Generation | Allocation Concealment | Selective reporting | ITT | Cohort representativeness | Comparator representativeness | Confounder Adjustment
Key Question 1
Biederman, 2008,; 18316421, NRCS | Unclear | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | N/A | N/A | N/A | N/A | N/A | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low concern) | Low RoB (NRCS)
Wilens 2006; 16601645, Single group | Unclear | Yes (High concern)^a^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | N/A | N/A | N/A | N/A | N/A | Yes (Low concern) | N/A | N/A | No (Low concern) | Moderate RoB (Single group)
Chang, 2014,; 25158998, NRCS | Unclear | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | N/A | N/A | N/A | N/A | N/A | Yes (Low concern) | Unclear | Yes (Low concern) | No (Low concern) | Moderate RoB (NRCS)
Dalsgaard, 2014,; 24090624, Single group | Unclear | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | N/A | N/A | N/A | N/A | N/A | No (High concern)^b^ | N/A | N/A | No (Low concern) | Moderate RoB (Single group)
Mannuzza, 2008,; 18381904, Single group | Yes (Low concern) | No (Low concern) | No (High concern)^c^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | N/A | N/A | N/A | N/A | N/A | Yes (Low concern) | N/A | N/A | No (Low concern) | Moderate RoB (Single Group)
Steinhausen 2014; 24314850, NRCS | Unclear | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | N/A | N/A | N/A | N/A | N/A | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low concern) | Low RoB (NRCS)
Torgersen 2013; 23104523, Single group | Unclear | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | N/A | N/A | N/A | N/A | N/A | Yes (Low concern) | N/A | N/A | No (Low concern) | Low RoB (Single group)
Key Question 2
Levin 2006; 16102908, RCT | Unclear | Yes (High concern)^d^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Unclear | Unclear | No (Low concern) | Yes (Low concern) | N/A | NA | N/A | No (Low concern) | Moderate RoB (RCT)
Levin 2007; 16930863, RCT | Unclear | Yes (High concern)^e^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Unclear | Unclear | No (Low concern) | Yes (Low concern) | N/A | N/A | N/A | No (Low concern) | Moderate RoB (RCT)
Levin 2015; 25887096, RCT | Yes (Low concern) | Yes (High concern)^f^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low concern) | Yes (Low concern) | N/A | N/A | N/A | No (Low concern) | Moderate RoB (RCT)
Notzon 2016; 28051838, RCT | Yes (Low concern) | Yes (High concern)^g^ | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low concern) | Yes (Low concern) | N/A | N/A | N/A | No (Low concern) | Moderate RoB (RCT)
Konstenius 2010; 20015599, RCT | Unclear | No (Low concern) | Unclear (NR) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | No (Low concern) | Yes (Low concern) | N/A | N/A | N/A | No (Low concern) | Low RoB (RCT)
Kast 2021; 33988929, NRCS | Unclear | No (Low concern) | No (High Concern^h^ | No (High concern)^i^ | Yes (Low concern) | No (High concern^j^ | N/A | N/A | N/A | N/A | N/A | Yes (Low concern) | Yes (Low concern) | No (High concern)^k^ | No (Low concern) | High RoB (RCT)
Schubiner 2002; 12233989, RCT | Yes (Low concern) | No (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | Yes (Low concern) | N/A | N/A | N/A | No (Low concern) | Low RoB (RCT)

Notes. Co-publications are Biederman-2008 and Wilens-2006, Levin-2015 and Notzon-2016.

a Low retention at 10 years of follow-up (55 out of 140);

b Cases with high severity of ADHD;

c Poorly reported overall methods and results;

d Only 25/33, 21/32, and 23/33 patients completed the 12 weeks of the trial for the placebo, MPH, and BPR groups;

e Only 44% of patients completed the entire 14-week trial;

f Thirty-three participants (26.2%) dropped out prior to maintenance phase completion (end of week 13);

g The dropout rate in the placebo group was 30% compared to a dropout rate of 24.3% in the active arm;

h Outcome and comparison groups were not clear;

i It was not clear which diagnoses of ADHD were used when/in what way;

j There was no clear definition of “retention”;

k Crude analysis.

Abbreviations. N/A=not applicable; NRCs=non-randomized comparative study; ROB=risk of bias.