# APPENDIX B STUDIES EXCLUDED DURING FULL-TEXT SCREENING

Citation and Reason for Exclusion
Abel KF, Bramness JG, Martinsen EW. Stimulant medication for ADHD in opioid maintenance treatment. Journal of Dual Diagnosis. 2014;10(1):32–38. doi:10.1080/15504263.2013.867657. Single group (KQ2).25392060
Adler LA, Lynch LR, Shaw DM, . Medication adherence and symptom reduction in adults treated with mixed amphetamine salts in a randomized crossover study. Postgraduate Medicine. September 2011;123(5):71–79. No SUD population (KQ2).
Aharonovich E, Garawi F, Bisaga A, . Concurrent cannabis use during treatment for comorbid ADHD and cocaine dependence: Effects on outcome. The American Journal of Drug and Alcohol Abuse. 2006;32(4):629–635. doi:10.1080/00952990600919005. No analysis by stimulant medication status.17127551
Ang A, Hillhouse M, Jenkins J, Reed S, Ling W. Methylphenidate for methamphetamine use disorders in participants with and without ADHD. Journal article; Conference proceeding. Drug and Alcohol Dependence. 2015;156:e7. doi:10.1016/j.drugalcdep.2015.07.938. No outcomes of SUD, misuse, diversion (KQ1).
Barkley RA, Fischer M, Smallish L, Fletcher K. Does the treatment of attention-deficit/hyperactivity disorder with stimulants contribute to drug use/abuse? A 13-year prospective study. Pediatrics. 01 Jan 2003;111(1):97–109. ADHD not diagnosed by DSM or some other inventory, or majority not ADHD.12509561
Bejerot S, Rydén EM, Arlinde CM. Two-year outcome of treatment with central stimulant medication in adult attention-deficit/hyperactivity disorder: A prospective study. The Journal of Clinical Psychiatry. 2010;71(12):1590–1597. doi:10.4088/JCP.09m05168pur. No outcomes of SUD, misuse, diversion (KQ1).20584517
Biederman J. Pharmacotherapy for attention-deficit/hyperactivity disorder (ADHD) decreases the risk for substance abuse: Findings from a longitudinal follow-up of youths with and without ADHD. The Journal of Clinical Psychiatry. 2003;64(Suppl11):3–8. Outcome not in adults (or majority not in adults).
Biederman J, Krishnan S, Zhang Y, McGough JJ, Findling RL. Efficacy and tolerability of lisdexamfetamine dimesylate (NRP-104) in children with attention-deficit/hyperactivity disorder: A phase III, multicenter, randomized, double-blind, forced-dose, parallel-group study. Clinical Therapeutics: The International Peer-Reviewed Journal of Drug Therapy. 2007;29(3):450–463. doi:10.1016/S0149-2918(07)80083-X. Outcome not in adults (or majority not in adults).
Biederman J, Wilens T, Mick E, Spencer T, Faraone SV. Pharmacotherapy of attention-deficit/hyperactivity disorder reduces risk for substance use disorder. Pediatrics. 1999 Aug 1;104(2):e20-. No analysis by stimulant medication status.10429138
Biederman J, Petty CR, Monuteaux MC, . Adult psychiatric outcomes of girls with attention deficit hyperactivity disorder: 11-year follow-up in a longitudinal case-control study. Am J Psychiatry. Apr 2010;167(4):409–17. doi:10.1176/appi.ajp.2009.09050736. No analysis by stimulant medication status.20080984
Bihlar Muld B, Jokinen J, Bolte S, Hirvikoski T. Long-term outcomes of pharmacologically treated versus non-treated adults with ADHD and substance use disorder: A naturalistic study. Journal of Substance Abuse Treatment. 01 Apr 2015;51:82–90. Inpatient or incarcerated sample.25491733
Blevins D, Choi CJ, Pavlicova M, . Impulsiveness as a moderator of amphetamine treatment response for cocaine use disorder among ADHD patients. Drug and Alcohol Dependence. 2020;213doi:10.1016/j.drugalcdep.2020.108082. No analysis by stimulant medication status.
Boland H, DiSalvo M, Fried R, . A literature review and meta-analysis on the effects of ADHD medications on functional outcomes. J Psychiatr Res. Apr 2020;123:21–30. doi:10.1016/j.jpsychires.2020.01.006. Systematic Review.32014701
Brancati GE, De Dominicis F, Petrucci A, . Long-term treatment of adult ADHD in a naturalistic setting: Clinical predictors of attrition, medication choice, improvement, and response. The World Journal of Biological Psychiatry. 2023;24(6):523–538. doi:10.1080/15622975.2023.2168750. No analysis by stimulant medication status.36637001
Breyer JL, Lee S, Winters KC, August GJ, Realmuto GM. A longitudinal study of childhood ADHD and substance dependence disorders in early adulthood. Psychology of Addictive Behaviors. 2014;28(1):238–246. doi:10.1037/a0035664. No analysis by stimulant medication status.24731117
Calver J, Sanfilippo F, Preen D, Bulsara M. Prescribed stimulant use by Western Australians with Attention Deficit Hyperactivity Disorder (ADHD): Does amount dispensed exceed the expected authorised use? Australian and New Zealand Journal of Public Health. December 2007;31(6):533–539. No outcomes of SUD, misuse, diversion (KQ1).18081573
Carpentier PJ, de Jong CA, Dijkstra BA, Verbrugge CA, Krabbe PF. A controlled trial of methylphenidate in adults with attention deficit/hyperactivity disorder and substance use disorders. Addiction. Dec 2005;100(12):1868–74. doi:10.1111/j.1360-0443.2005.01272.x. Inpatient or incarcerated sample.16367988
Carpentier PJ, Levin FR. Pharmacological treatment of ADHD in addicted patients: what does the literature tell us? Harvard Review of Psychiatry. 01 Mar 2017;25(2):50–64. Systematic Review.28272130
Castells X, Ramos-Quiroga JA, Rigau D, . Efficacy of methylphenidate for adults with attention-deficit hyperactivity disorder: A meta-regression analysis. CNS Drugs. 2011;25(2):157–169. doi:10.2165/11539440-000000000-00000. Systematic Review.21254791
Cepeda MS, Fife D, Berwaerts J, Friedman A, Yuan Y, Mastrogiovanni G. Doctor shopping for medications used in the treatment of attention deficit hyperactivity disorder: shoppers often pay in cash and cross state lines. The American Journal of Drug and Alcohol Abuse. 2015;41(3):226–229. doi:10.3109/00952990.2014.945591. No analysis by stimulant medication status.25860878
Cepeda MS, Fife D, Berwaerts J, Yuan Y, Mastrogiovanni G. Shopping behavior for ADHD drugs: results of a cohort study in a pharmacy database. Drugs in R&D. 01 Sep 2014;14(3):205–211. ADHD not diagnosed by DSM or some other inventory, or majority not ADHD.25118848
Chang Z, Quinn PD, O’Reilly L, . Medication for attention-deficit/hyperactivity disorder and risk for suicide attempts. Biological Psychiatry. 2020;88(6):452–458. doi:10.1016/j.biopsych.2019.12.003. No outcomes of SUD, misuse, diversion (KQ1).31987492
Chaulagain A, Lyhmann I, Halmøy A, . A systematic meta-review of systematic reviews on attention deficit hyperactivity disorder. Eur Psychiatry. Nov 17 2023;66(1):e90. doi:10.1192/j.eurpsy.2023.2451. Systematic Review.37974470
Cook J, Lloyd-Jones M, Arunogiri S, Ogden E, Bonomo Y. Managing attention deficit hyperactivity disorder in adults using illicit psychostimulants: A systematic review. Australian and New Zealand Journal of Psychiatry. 2017;51(9):876–885. doi:10.1177/0004867417714878. Systematic Review.28639480
Cunill R, Castells X, Tobias A, Capellà D. Pharmacological treatment of attention deficit hyperactivity disorder with co-morbid drug dependence. Journal of Psychopharmacology. 2015;29(1):15–23. doi:10.1177/0269881114544777. Systematic Review.25142405
Dalsgaard S, Mortensen PB, Frydenberg M, Thomsen PH. ADHD, stimulant treatment in childhood and subsequent substance abuse in adulthood—A naturalistic long-term follow-up study. Addictive Behaviors. 2014;39(1):325–328. doi:10.1016/j.addbeh.2013.09.002. Duplicate.24090624
Darredeau C, Barrett SP, Jardin B, Pihl RO. Patterns and predictors of medication compliance, diversion, and misuse in adult prescribed methylphenidate users. Human Psychopharmacology: Clinical and Experimental. 2007;22(8):529–536. doi:10.1002/hup.883. No longitudinal data.17910020
DiSalvo M. Quantifying the protective effects of stimulants on functional outcomes in ADHD: A focus on number-needed-to-treat statistic and sex effects. Journal article; Conference proceeding. Journal of the American Academy of Child and Adolescent Psychiatry. 2020;59(10):S317. doi:10.1016/j.jaac.2020.07.745. Other.
Downey KK, Sclrubiner H, Schuster CR. Double-blind placebo controlled stimulant trial for cocaine dependent ADHD adults. Journal article. NIDA research monograph. 2000;180:116. Unable to locate/ Conference abstract without useable data.
Fairman KA, Davis LE, Peckham AM, Sclar DA. Diagnoses of cardiovascular disease or substance addiction/abuse in US adults treated for ADHD with stimulants or atomoxetine: is use consistent with product labeling? Drugs - Real World Outcomes. 01 Mar 2018;5(1):69–79. Not incident SUD for KQ1 (had SUD at baseline).29305714
Faraone SV, Biederman J, Wilens TE, Adamson J. A naturalistic study of the effects of pharmacotherapy on substance use disorders among ADHD adults. Psychological Medicine. 2007;37(12):1743–1752. doi:10.1017/S0033291707000335. No longitudinal data.17349106
Faraone SV, Upadhyaya HP. The effect of stimulant treatment for ADHD on later substance abuse and the potential for medication misuse, abuse, and diversion. The Journal of clinical psychiatry. Nov 2007;68(11):e28. Unable to locate/ Conference abstract without useable data.18052554
Faraone SV, Wilens T. Does stimulant treatment lead to substance use disorders? The Journal of Clinical Psychiatry. 2003;64(Suppl11):9–13. Systematic Review.
Fischer M, Barkley RA. Childhood stimulant treatment and risk for later substance abuse. J Clin Psychiatry. 2003;64 Suppl 11:19–23. ADHD not diagnosed by DSM or some other inventory, or majority not ADHD.
Fouladvand S, Hankosky ER, Bush H, . Predicting substance use disorder using long-term attention deficit hyperactivity disorder medication records in Truven. Health informatics journal. 01 Jun 2020;26(2):787–802. No analysis by stimulant medication status.31106686
Franck J, Konstenius M, Jayaram-Lindstrom N, Philips B, Guterstam J. ADHD in drug addiction: a RCT on the feasibility of methylphenidate treatment in criminal amphetamine users. Journal article; Conference proceeding. International journal of neuropsychopharmacology. 2012;15:41. doi:10.1017/S1461145712000508. Inpatient or incarcerated sample.21439107
Frauger E, Pauly V, Natali F, . Patterns of methylphenidate use and assessment of its abuse and diversion in two French administrative areas using a proxy of deviant behaviour determined from a reimbursement database: Main trends from 2005 to 2008. CNS Drugs. 2011;25(5):415–424. doi:10.2165/11587640-000000000-00000. ADHD not diagnosed by DSM or some other inventory, or majority not ADHD.21476612
Gao L, Man KKC, Tse ML, . Descriptive analysis of poisoning cases involving attention deficit hyperactivity disorder medications in Hong Kong. Hong Kong Med J. Jun 2023;29(3):224–232. doi:10.12809/hkmj219624. No longitudinal data.37303104
Gau SS-F, Ni H-C, Shang C-Y, . Psychiatric comorbidity among children and adolescents with and without persistent attention-deficit hyperactivity disorder. Australian and New Zealand Journal of Psychiatry. 2010;44(2):135–143. doi:10.3109/00048670903282733. Outcome not in adults (or majority not in adults).20113302
Gilder DA, Gizer IR, Lau P, Ehlers CL. Stimulant dependence and stimulant-associated psychosis: clinical characteristics and age of onset in a native American community sample. J Addict Med. Jul–Aug 2014;8(4):241–8. doi:10.1097/adm.0000000000000039. No longitudinal data.24755633
Goksøyr PK, Nøttestad JA. The burden of untreated ADHD among adults: The role of stimulant medication. Addictive Behaviors. 2008;33(2):342–346. doi:10.1016/j.addbeh.2007.09.008. No longitudinal data.17920777
Gonzalez RA, Velez-Pastrana MC, Blankers M, . Onset and severity of early disruptive behavioral disorders in treatment-seeking substance use disorder patients with and without Attention-Deficit/Hyperactivity Disorder. European Addiction Research. 01 Aug 2020;26(4–5):211–222. Single group (KQ2).32594079
Groenman AP, Oosterlaan J, Rommelse NNJ, . Stimulant treatment for attention-deficit hyperactivity disorder and risk of developing substance use disorder. The British Journal of Psychiatry. 2013;203(2):112–119. doi:10.1192/bjp.bp.112.124784. Outcome not in adults (or majority not in adults).23846996
Groenman AP, Schweren LJS, Weeda W, . Stimulant treatment profiles predicting co-occurring substance use disorders in individuals with attention-deficit/hyperactivity disorder. European Child & Adolescent Psychiatry. 2019;28(9):1213–1222. doi:10.1007/s00787-019-01283-y. Outcome not in adults (or majority not in adults).30721356
Gudmundsdottir BG, Weyandt L, Ernudottir GB. Prescription stimulant misuse and ADHD symptomatology among college students in Iceland. Journal of Attention Disorders. 2020;24(3):384–401. doi:10.1177/1087054716684379. No longitudinal data.28013572
Harty SC, Ivanov I, Newcorn JH, Halperin JM. The impact of conduct disorder and stimulant medication on later substance use in an ethnically diverse sample of individuals with attention-deficit/hyperactivity disorder in childhood. Journal of Child and Adolescent Psychopharmacology. 2011;21(4):331–339. doi:10.1089/cap.2010.0074. Outcome not in adults (or majority not in adults).21823914
Humphreys KL, Eng T, Lee SS. Stimulant medication and substance use outcomes: A meta-analysis. JAMA Psychiatry. 2013;70(7):740–749. doi:10.1001/jamapsychiatry.2013.1273. Systematic Review.23754458
Huss M. ADHD and substance abuse. In: IX Annual European Congress of Psychiatry. Hamburg, Germany; 1999. Unable to locate/ Conference abstract without useable data.
Huss M. The relationship of ADHD and substance abuse. Presented at the International Conference on ADHD; February 26-March 1, 2003; Chicago, IL. Unable to locate/ Conference abstract without useable data.
Jasinski DR, Krishnan SS. Abuse liability and safety of oral lisdexamfetamine dimesylate in individuals with a history of stimulant abuse. Journal of Psychopharmacology. June 2009;23(4):419–427. Non-ADHD population.19329547
Jean FAM, Moulin F, Schwartz AN, . Association between ADHD symptoms and illicit stimulants use following 1 year among French university students of the i-Share cohort. Soc Psychiatry Psychiatr Epidemiol. 2024;59(5):887–897. doi:10.1007/s00127-023-02499-9. ADHD not diagnosed by DSM or some other inventory, or majority not ADHD.37268785
Jerrell JM, McIntyre RS, Park Y-MM. Risk factors for incident major depressive disorder in children and adolescents with attention-deficit/hyperactivity disorder. European Child & Adolescent Psychiatry. 2015;24(1):65–73. doi:10.1007/s00787-014-0541-z. Outcome not in adults (or majority not in adults).24705730
Katusic SK, Barbaresi WJ, Colligan RC, Weaver AL, Leibson CL, Jacobsen SJ. Psychostimulant treatment and risk for substance abuse among young adults with a history of attention-deficit/hyperactivity disorder: A population-based, birth cohort study. Journal of Child and Adolescent Psychopharmacology. 2005;15(5):764–776. doi:10.1089/cap.2005.15.764. Outcome not in adults (or majority not in adults).16262593
Kollins SH, Youcha S, Lasser R, Thase ME. Lisdexamfetamine dimesylate for the treatment of attention deficit hyperactivity disorder in adults with a history of depression or history of substance use disorder. Innovations in Clinical Neuroscience. 2011;8(2):28–32. No SUD population (KQ2).21468295
Konstenius M, Jayaram-Lindstrom N, Guterstam J, Beck O, Philips B, Franck J. Methylphenidate for attention deficit hyperactivity disorder and drug relapse in criminal offenders with substance dependence: a 24-week randomized placebo-controlled trial. Addiction (Abingdon, England). 01 Mar 2014;109(3):440–449. Inpatient or incarcerated sample.24118269
Kuntsi J, Larsson H, Deng Q, Lichtenstein P, Chang Z. The combined effects of young relative age and Attention-Deficit/Hyperactivity Disorder on negative long-term outcomes. Journal of the American Academy of Child and Adolescent Psychiatry. February 2022;61(2):291–297. Outcome not in adults (or majority not in adults).34389201
Lambert N. The contribution of childhood ADHD, conduct problems, and stimulant treatment to adolescent and adult tobacco and psychoactive substance abuse. Ethical Human Psychology and Psychiatry: An International Journal of Critical Inquiry. Fal-Win 2005 2005;7(3):197–221. doi:10.1891/1559-4343.7.3.197. Not exclusive to ADHD.
Lambert NM, Hartsough CS. Prospective study of tobacco smoking and substance dependencies among samples of ADHD and non-ADHD participants. Journal of learning disabilities. 1998 Nov;31(6):533–44. Conducted before 1994.9813951
Levin FR. Methylphenidate Treatment for Cocaine Abuse and ADHD – 1. ClinicalTrials.gov identifier: NCT00136734. Duplicate.
Levin FR. Study of Adderall-XR for the Treatment of Adult Attention Deficit Hyperactivity Disorder and Cocaine Dependence (CAMP). ClinicalTrials.gov identifier: NCT00553319. Duplicate.
Levin FR, Bisaga A, Raby W, . Effects of major depressive disorder and attention-deficit/hyperactivity disorder on the outcome of treatment for cocaine dependence. Journal of Substance Abuse Treatment. 2008;34(1):80–89. doi:10.1016/j.jsat.2006.11.012. Other.17574796
Levin FR, Choi CJ, Pavlicova M, . How treatment improvement in ADHD and cocaine dependence are related to one another: A secondary analysis. Drug and Alcohol Dependence. 2018;188:135–140. doi:10.1016/j.drugalcdep.2018.03.043. Other.29775957
Levin FR, Evans SM, McDowell DM, Brooks DJ, Nunes E. Bupropion treatment for cocaine abuse and adult attention-deficit/hyperactivity disorder. Journal of Addictive Diseases. 2002;21(1):1–16. No SUD population (KQ2).
Levin FR, Mariani JJ, Mahony A, . Mixed amphetamine salts-extended release for ADHD adults with cocaine use disorder. Journal article; Conference proceeding. Drug and alcohol dependence. 2015;146:e175. doi:10.1016/j.drugalcdep.2014.09.393. Unable to locate/ Conference abstract without useable data.
Levin FR, Mariani JJ, Specker S, . Extended-release mixed amphetamine salts vs placebo for comorbid adult attention-deficit/hyperactivity disorder and cocaine use disorder: A randomized clinical trial. JAMA Psychiatry. 2015;72(6):593–602. doi:10.1001/jamapsychiatry.2015.41. Duplicate.25887096
Levy S, Katusic SK, Colligan RC, . Childhood ADHD and risk for substance dependence in adulthood: A longitudinal, population-based study. PLoS ONE. 27 Aug 2014;9(8) (no pagination)e105640. No analysis by stimulant medication status.25162629
Loney J, Kramer JR, Salisbury H. Medicated versus unmedicated ADHD children: adult involvement with legal and illegal drugs. Attention Deficit Hyperactivity Disorder: State of the Science. 2002:1–6. Review article (non-systematic).
Loney J, Whaley-Klahn MA, Kosier T, Conboy J. Hyperactive boys and their brothers at 21: predictors of aggressive and antisocial outcomes. Prospective studies of crime and delinquency. 1983:181–207. Conducted before 1994.
Loney J. Risk of treatment versus nontreatment. InNIH Consensus Development Conference on Diagnosis and Treatment of Attention Deficit Hyperactivity Disorder 1998 Nov 16 (p. 175). Unable to locate/ Conference abstract without useable data.
Martinez-Raga J, Knecht C, De Alvaro R, Szerman N, Ruiz P. Addressing dual diagnosis patients suffering from attention-deficit hyperactivity disorders and comorbid substance use disorders: A review of treatment considerations. Addictive Disorders and their Treatment. December 2013;12(4):213–230. Systematic Review.
McCabe SE, Dickinson K, West BT, Wilens TE. Age of onset, duration, and type of medication therapy for attention-deficit/hyperactivity disorder and substance use during adolescence: A multi-cohort national study. Journal of the American Academy of Child & Adolescent Psychiatry. 2016;55(6):479–486. doi:10.1016/j.jaac.2016.03.011. No longitudinal data.27238066
McCabe SE, Figueroa O, McCabe VV, . Is age of onset and duration of stimulant therapy for ADHD associated with cocaine, methamphetamine, and prescription stimulant misuse? Journal of child psychology and psychiatry, and allied disciplines. 2023;16. No longitudinal data.
McCabe SE, Veliz P, Wilens TE, Schulenberg JE. Adolescents’ prescription stimulant use and adult functional outcomes: A national prospective study. Journal of the American Academy of Child & Adolescent Psychiatry. 2017;56(3):226–233. doi:10.1016/j.jaac.2016.12.008. Non-ADHD population.28219488
McRae-Clark AL, Carter RE, Killeen TK, Carpenter MJ, White KG, Brady KT. A placebo-controlled trial of atomoxetine in marijuana-dependent individuals with attention deficit hyperactivity disorder. Am J Addict. Nov–Dec 2010;19(6):481–9. doi:10.1111/j.1521-0391.2010.00076.x. No use of stimulants.20958842
Merrill RM, Thygerson SM, Palmer CA. Risk of injury according to attention deficit hyperactivity disorder, comorbid mental illness, and medication therapy. Pharmacopsychiatry. 2016;49(2):45–50. doi:10.1055/s-0035-1565132. No SUD population (KQ2).26829453
Mitchell HM, Park G, Hammond CJ. Are non-abstinent reductions in World Health Organization drinking risk level a valid treatment target for alcohol use disorders in adolescents with ADHD? Addictive Behaviors Reports. 2020;12doi:10.1016/j.abrep.2020.100312. Outcome not in adults (or majority not in adults).
Moffitt TE, Houts R, Asherson P, . Is adult ADHD a childhood-onset neurodevelopmental disorder? Evidence from a four-decade longitudinal cohort study. American Journal of Psychiatry. 01 Oct 2015;172(10):967–977. <10 patients eligible.25998281
Moggi F, Schorno D, Soravia LM, . Screened attention deficit/hyperactivity disorder as a predictor of substance use initiation and escalation in early adulthood and the role of self-reported conduct disorder and sensation seeking: A 5-year longitudinal study with young adult Swiss men. European Addiction Research. 2020;26(4–5):233–244. doi:10.1159/000508304. No use of stimulants.32564034
Molina BSG, Hinshaw SP, Arnold LE, . Adolescent substance use in the multimodal treatment study of attention-deficit/hyperactivity disorder (ADHD) (MTA) as a function of childhood ADHD, random assignment to childhood treatments, and subsequent medication. Journal of the American Academy of Child & Adolescent Psychiatry. 2013;52(3):250–263. doi:10.1016/j.jaac.2012.12.014. Outcome not in adults (or majority not in adults).23452682
Molina BSG, Kennedy TM, Howard AL, . Association between stimulant treatment and substance use through adolescence into early adulthood. JAMA Psychiatry. Sep 1 2023;80(9):933–941. doi:10.1001/jamapsychiatry.2023.2157. No outcomes of SUD, misuse, diversion (KQ1).37405756
Molina BSG, Lindstrom RA, Pedersen SL, . Alcohol use by adolescents prescribed stimulants for ADHD increases risk of diversion. Journal article; Conference proceeding. Alcoholism: clinical and experimental research. 2020;44:131A. doi:10.1111/acer.14356. Outcome not in adults (or majority not in adults).
Molina B, Pelham W, Roth J. Stimulant medication and substance use by adolescents with a childhood history of ADHD. InPoster presented at the Biennial Meeting of the International Society for Research in Child and Adolescent Psychopathology 1999 Jul 16. Unable to locate/ Conference abstract without useable data.
Moran LV, Ongur D, Hsu J, Castro VM, Perlis RH, Schneeweiss S. Psychosis with methylphenidate or amphetamine in patients with ADHD. New England Journal of Medicine. 2019;380(12):1128–1138. No outcomes of SUD, misuse, diversion (KQ1).30893533
Musser CJ, Ahmann PA, Theye FW, Mundt P, Broste SK, Mueller-Rizner N. Stimulant use and the potential for abuse in Wisconsin as reported by school administrators and longitudinally followed children. Journal of Developmental and Behavioral Pediatrics. 1998;19(3):187–192. doi:10.1097/00004703-199806000-00006. Outcome not in adults (or majority not in adults).9648044
Najib J. The efficacy and safety profile of lisdexamfetamine dimesylate, a prodrug of d-amphetamine, for the treatment of attention-deficit/hyperactivity disorder in children and adults. Clinical Therapeutics. January 2009;31(1):142–176. Review article (non-systematic).19243715
Najib J, Didenko E, Meleshkina D, . Review of lisdexamfetamine dimesylate in children and adolescents with attention deficit/hyperactivity disorder. Curr Med Res Opin. Oct 2020;36(10):1717–1735. doi:10.1080/03007995.2020.1815002. Review article (non-systematic).32845786
Notzon DP, Mariani JJ, Pavlicova M, . Mixed-amphetamine salts increase abstinence from marijuana in patients with co-occurring attention-deficit/hyperactivity disorder and cocaine dependence. The American Journal on Addictions. 2016;25(8):666–672. doi:10.1111/ajad.12467. Duplicate.28051838
Ozgen H, Spijkerman R, Noack M, . Treatment of adolescents with concurrent substance use disorder and attention-deficit/hyperactivity disorder: A systematic review. Journal of Clinical Medicine. 01 Sep 2021;10(17) (no pagination)3908. Systematic Review.34501355
Pallucchini A, Carli M, Maremmani AGI, Scarselli M, Perugi G, Maremmani I. Influence of substance use disorder on treatment retention of adult-attention-deficit/hyperactive disorder patients. A 5-year follow-up study. Journal of Clinical Medicine. 01 May 2021;10(9) (no pagination)1984. No analysis by stimulant medication status.34063121
Paterson R, Douglas C, Hallmayer J, Hagan M, Krupenia Z. A randomised, double-blind, placebo-controlled trial of dexamphetamine in adults with attention deficit hyperactivity disorder. Australian and New Zealand Journal of Psychiatry. 1999;33(4):494–502. doi:10.1046/j.1440-1614.1999.00590.x. No outcomes of SUD, misuse, diversion (KQ1).10483843
Peterson K, McDonagh MS, Fu R. Comparative benefits and harms of competing medications for adults with attention-deficit hyperactivity disorder: A systematic review and indirect comparison meta-analysis. Psychopharmacology. 2008;197(1):1–11. doi:10.1007/s00213-007-0996-4. Systematic Review.18026719
Pham T, Milanaik R, Kaplan A, Papaioannou H, Adesman A. Household diversion of prescription stimulants: Medication misuse by parents of children with attention-deficit/hyperactivity disorder. Journal of Child and Adolescent Psychopharmacology. 2017;27(8):741–746. doi:10.1089/cap.2016.0058. No longitudinal data.28686059
Quinn PD, Chang Z, Hur K, . ADHD medication and substance-related problems. The American Journal of Psychiatry. 2017;174(9):877–885. doi:10.1176/appi.ajp.2017.16060686. No analysis by stimulant medication status.28659039
Rao K, Carpenter DM, Campbell CI. Attention-Deficit/Hyperactivity Disorder medication adherence in the transition to adulthood: associated adverse outcomes for females and other disparities. Journal of Adolescent Health. November 2021;69(5):806–814. No analysis by stimulant medication status.
Rasmussen K, Palmstierna T, Levander S. Differences in psychiatric problems and criminality between individuals treated with central stimulants before and after adulthood. Journal of Attention Disorders. 2019;23(2):173–180. doi:10.1177/1087054715571740. Not incident SUD for KQ1 (had SUD at baseline).25795454
Riggs PD, Hall SK, Mikulich-Gilbertson SK, Lohman M, Kayser A. A randomized controlled trial of pemoline for attention-deficit/hyperactivity disorder in substance-abusing adolescents. Journal of the American Academy of Child & Adolescent Psychiatry. 2004;43(4):420–429. doi:10.1097/00004583-200404000-00008. Outcome not in adults (or majority not in adults).15187802
Riggs PD, Winhusen T, Davies RD, . Randomized controlled trial of osmotic-release methylphenidate with cognitive-behavioral therapy in adolescents with Attention-Deficit/Hyperactivity Disorder and substance use disorders. Journal of the American Academy of Child & Adolescent Psychiatry. 2011;50(9):903–914. doi:10.1016/j.jaac.2011.06.010. Outcome not in adults (or majority not in adults).21871372
Scherrer JF, Salas J, Grucza R, . Prescription stimulant use during long-term opioid therapy and risk for opioid use disorder. Drug and Alcohol Dependence Reports. December 2022;5 (no pagination)100122. No analysis by stimulant medication status.36844161
Schubiner H, Downey KK, Arfken CL, . Double-blind placebo-controlled trial of methylphenidate in the treatment of adult ADHD patients with comorbid cocaine dependence. Experimental and Clinical Psychopharmacology. 2002;10(3):286–294. Clinical Research in Psychopharmacology and Substance Abuse. doi:10.1037/1064-1297.10.3.286. Duplicate.12233989
Semerci B, Taskiran S, Tufan E, Sanli I. Factors predicting treatment adherence in patients with adult attention-deficit/hyperactivity disorder: a preliminary study. ADHD Attention Deficit and Hyperactivity Disorders. 01 Sep 2016;8(3):139–147. No SUD population (KQ2).27056071
Sepúlveda DR, Thomas LM, McCabe SE, Cranford JA, Boyd CJ, Teter CJ. Misuse of prescribed stimulant medication for ADHD and associated patterns of substance use: preliminary analysis among college students. Journal of Pharmacy Practice. 2011;24(6):551–560. doi:10.1177/0897190011426558. No longitudinal data.22095577
Siffel C, DerSarkissian M, Kponee-Shovein K, . Suicidal ideation and attempts in the United States of America among stimulant-treated, non-stimulant-treated, and untreated patients with a diagnosis of attention-deficit/hyperactivity disorder. Journal of Affective Disorders. 2020;266:109–119. doi:10.1016/j.jad.2020.01.075. Not incident SUD for KQ1 (had SUD at baseline).32063553
Simpson D, Plosker GL. Atomoxetine: a review of its use in adults with attention deficit hyperactivity disorder. Drugs. 2004;64(2):205–22. doi:10.2165/00003495-200464020-00005. Review article (non-systematic).14717619
Skoglund C, Brandt L, Almqvist C, . Factors associated with adherence to methylphenidate treatment in adult patients with attention-deficit/hyperactivity disorder and substance use disorders. Journal of Clinical Psychopharmacology. 2016;36(3):222–228. ADHD not diagnosed by DSM or some other inventory, or majority not ADHD.27043119
Skoglund C, Kopp Kallner H, Skalkidou A, . Association of Attention-Deficit/Hyperactivity Disorder with teenage birth among women and girls in Sweden. JAMA Network Open. 10 Oct 2019;2(10) (no pagination)e1912463. No analysis by stimulant medication status.31577361
Sou B, Glass A, Brooks DJ, . Cigarette smoking trajectories among comorbid cocaine-dependent and attention deficit/hyperactivity-disorder individuals treated with extended-release mixed amphetamine salts. Journal article; Conference proceeding. Drug and alcohol dependence. 2015;156:e208–e209. doi:10.1016/j.drugalcdep.2015.07.562. No SUD population (KQ2).
Steinhausen H-C, Bisgaard C. Substance use disorders in association with attention-deficit/hyperactivity disorder, co-morbid mental disorders, and medication in a nationwide sample. European Neuropsychopharmacology. 2014;24(2):232–241. doi:10.1016/j.euroneuro.2013.11.003. Duplicate.24314850
Stephens JR, Heffner JL, Adler CM, . Risk and protective factors associated with substance use disorders in adolescents with first-episode mania. Journal of the American Academy of Child & Adolescent Psychiatry. 2014;53(7):771–779. doi:10.1016/j.jaac.2014.04.018. No analysis by stimulant medication status.24954826
Strålin P, Hetta J. First episode psychosis and comorbid ADHD, autism and intellectual disability. European Psychiatry. 2019;55:18–22. doi:10.1016/j.eurpsy.2018.09.007. Not incident SUD for KQ1 (had SUD at baseline).30384107
Sundquist J, Ohlsson H, Sundquist K, Kendler KS. Attention-deficit/hyperactivity disorder and risk for drug use disorder: A population-based follow-up and co-relative study. Psychological Medicine. 2015;45(5):977–983. doi:10.1017/S0033291714001986. Outcome not in adults (or majority not in adults).25119068
Uchida M, Spencer TJ, Faraone SV, Biederman J. Adult outcome of ADHD: An overview of results from the MGH longitudinal family studies of pediatrically and psychiatrically referred youth with and without ADHD of both sexes. Journal of Attention Disorders. 2018;22(6):523–534. doi:10.1177/1087054715604360. Review article (non-systematic).26396145
Vogel T, Dom G, Glind G, . Is attention deficit/hyperactivity disorder among men associated with initiation or escalation of substance use at 15-month follow-up? A longitudinal study involving young Swiss men. Addiction. 2016;111(10):1867–1878. doi:10.1111/add.13422. Not incident SUD for KQ1 (had SUD at baseline).27061514
Warden D, Riggs PD, Min SJ, . Major depression and treatment response in adolescents with ADHD and substance use disorder. Drug Alcohol Depend. Jan 1 2012;120(1–3):214–9. doi:10.1016/j.drugalcdep.2011.08.001. Outcome not in adults (or majority not in adults).21885210
Weber J, Siddiqui MA. Lisdexamfetamine dimesylate: in attention-deficit hyperactivity disorder in adults. CNS Drugs. 2009;23(5):419–25. doi:10.2165/00023210-200923050-00005. Review article (non-systematic).19453202
Weyandt LL, Oster DR, Marraccini ME, . Pharmacological interventions for adolescents and adults with ADHD: stimulant and nonstimulant medications and misuse of prescription stimulants. Psychology Research and Behavior Management. 2014;7. Systematic Review.
Wilens TE, Adamson J, Monuteaux MC, . Effect of prior stimulant treatment for attention-deficit/hyperactivity disorder on subsequent risk for cigarette smoking and alcohol and drug use disorders in adolescents. Archives of Pediatrics and Adolescent Medicine. October 2008;162(10):916–921. Outcome not in adults (or majority not in adults).18838643
Wilens TE, Adler LA, Adams J, . Misuse and diversion of stimulants prescribed for ADHD: A systematic review of the literature. Journal of the American Academy of Child & Adolescent Psychiatry. 2008;47(1):21–31. doi:10.1097/chi.0b013e31815a56f1. Systematic Review.18174822
Wilens TE, Adler LA, Tanaka Y, . Correlates of alcohol use in adults with ADHD and comorbid alcohol use disorders: exploratory analysis of a placebo-controlled trial of atomoxetine. Curr Med Res Opin. Dec 2011;27(12):2309–20. doi:10.1185/03007995.2011.628648. No use of stimulants.22029549
Wilens TE, Adler LA, Weiss MD, . Atomoxetine treatment of adults with ADHD and comorbid alcohol use disorders. Drug Alcohol Depend. Jul 1 2008;96(1–2):145–54. doi:10.1016/j.drugalcdep.2008.02.009. No use of stimulants.18403134
Wilens TE, Faraone SV, Biederman J, Gunawardene S. Does stimulant therapy of attention-deficit/hyperactivity disorder beget later substance abuse? A meta-analytic review of the literature. Pediatrics. Jan 2003;111(1):179–85. doi:10.1542/peds.111.1.179. Systematic Review.12509574
Wilens TE, Gignac M, Swezey A, Mounteaux MC, Biederman J. Characteristics of adolescents and young adults with ADHD who divert or misuse their prescribed medications. Journal of the American Academy of Child & Adolescent Psychiatry. 2006;45(4):408–414. doi:10.1097/01.chi.0000199027.68828.b3. Duplicate.16601645
Wilens TE, Monuteaux MC, Snyder LE, Moore H, Whitley J, Gignac M. The clinical dilemma of using medications in substance-abusing adolescents and adults with attention-deficit/hyperactivity disorder: what does the literature tell us? J Child Adolesc Psychopharmacol. Oct 2005;15(5):787–98. doi:10.1089/cap.2005.15.787. Systematic Review.16262595
Winhusen, T. Attention Deficit Hyperactivity Disorder (ADHD) in Adolescents With Substance Use Disorders (SUD). ClinicalTrials.gov identifier: NCT00264797. Duplicate.
Winters KC, Lee S, Botzet A, Fahnhorst T, Realmuto GM, August GJ. A Prospective Examination of the Association of Stimulant Medication History and Drug Use Outcomes among Community Samples of ADHD Youths. J Child Adolesc Subst Abuse. 2011;20(4):314–329. doi:10.1080/1067828x.2011.598834. ADHD not diagnosed by DSM or some other inventory, or majority not ADHD.22582022
Young S, Emilsson B, Sigurdsson JF, . A randomized controlled trial reporting functional outcomes of cognitive-behavioural therapy in medication-treated adults with ADHD and comorbid psychopathology. European Archives of Psychiatry and Clinical Neuroscience. 01 Apr 2017;267(3):267–276. No SUD population (KQ2).27752827

Notes. 16 records were excluded as duplicates during title and abstract cleaning, however 6 of those were found to be duplicates within.