# APPENDIX A SEARCH STRATEGIES

Search | | Search Statement | Results
PubMed | 1 | “Attention Deficit Disorder with Hyperactivity”[Mesh] OR “attention deficit hyperactivity disorder”[tiab] OR “ADHD”[tiab] OR “attention deficit disorder”[tiab] OR “ADDH” [tiab] OR “attention disorder” [tiab] OR “hyperactive disorder” [tiab] | 49,561
PubMed | 2 | “Attention Deficit Disorder with Hyperactivity/drug therapy”[Majr] OR “Central Nervous System Stimulants”[MeSH] OR “Methylphenidate”[MeSH] OR Dexmethylphenidate[MeSH] OR “Dextroamphetamine”[MeSH] OR “Adderall”[Supplementary Concept] OR “lisdexamfetamine dimesylate”[Supplementary Concept] OR “Amphetamine”[MeSH] OR “Central Nervous System Stimulants” [Pharmacological Action] OR “Central Nervous System Stimulants”[tiab] OR “psychostimulant”[tiab] OR “Methylphenidate”[tiab] OR “Methylphenidate Hydrochloride”[tiab] OR “Aptensio”[tiab] OR “Concerta”[tiab] OR “Ritalin”[tiab] OR “Ritalin LA”[tiab] OR “Medikinet”[tiab] OR “Equasym”[tiab] OR “Quillivant”[tiab] OR “Metadate”[tiab] OR “Daytrana”[tiab] OR Dexmethylphenidate OR “Dexmethylphenidate Hydrochloride”[tiab] OR “Focalin”[tiab] OR “Dextroamphetamine”[tiab] OR “Dexedrine”[tiab] OR Dextrostat OR “ProCentra”[tiab] OR “Zenzedi”[tiab] OR “mixed amphetamine salts”[tiab] OR “Adderall” [tiab] OR “lisdexamfetamine”[tiab] OR “lisdexamfetamine dimesylate”[tiab] OR “Vyvanse”[tiab] OR “Venvanse”[tiab] OR “Elvanse”[tiab] OR “Tyvense”[tiab] OR “Dyanavel”[tiab] OR “Evekeo”[tiab] OR “ADHD medications”[tiab] OR “Adzenys”[tiab] OR “Amfetamine”[tiab] OR “Amphetamine”[tiab] OR “amphetamine aspartate”[tiab] OR “Amphetamines”[tiab] OR “Aptensio”[tiab] OR “Biphentin”[tiab] OR “Central Nervous System Stimulants”[tiab] OR “Concerta”[tiab] OR “dexamfetamine”[tiab] OR “dexamphetamine”[tiab] OR “Dexedrine”[tiab] OR “Dexmethylphenidate”[tiab] OR “dextroamfetamine”[tiab] OR “Dextroamphetamine”[tiab] OR “Dyanavel”[tiab] OR “Equasym”[tiab] OR “Evekeo”[tiab] OR “Focalin”[tiab] OR “lisdexamfetamine”[tiab] OR “lisdexamphetamine”[tiab] OR “Medikinet”[tiab] OR “Metadate”[tiab] OR “Methamphetamine”[tiab] OR “methylfenidate”[tiab] OR “Methylin”[tiab] OR “methylphenidate”[tiab] OR “ProCentra”[tiab] OR “QuilliChew”[tiab] OR “Quillivant”[tiab] OR “Ritalin”[tiab] OR “Stimulant”[tiab] OR “Vyvanse”[tiab] OR “Zenzedi”[tiab] | 139,188
PubMed | 3 | “Substance-Related Disorders”[Mesh] OR “Drug abuse” OR “drug misuse” OR “drug dependence” OR “drug addiction” OR “substance use disorder” OR “substance abuse” OR “substance misuse” OR “substance dependence” OR “substance addiction” OR “prescription abuse” OR “Alcoholism”[Mesh] OR “cannabis use disorder” OR “alcohol use disorder” OR “stimulant use disorder” OR “hallucinogen use disorder” OR “opioid use disorder” OR “inhalant use disorder” OR “diversion”[tiab] OR “illicit drug use”[tiab] OR “illegal drug use”[tiab] OR “problem substance use”[tiab] OR “problematic substance use”[tiab] OR “risky substance use”[tiab] OR “substance use consequences”[tiab] or ((Alcohol OR “Alcoholic Beverages”[Mesh] OR cannabis OR Marijuana OR “Cannabis”[Mesh] OR “Marijuana Abuse”[Mesh] OR “Marijuana Smoking”[Mesh] OR opioids OR “Narcotics”[Mesh] OR “Analgesics, Opioid”[Mesh] OR kratom OR hallucinogens OR “Psychotropic Drugs”[Mesh] OR inhalants OR toluene OR stimulants OR “Central Nervous System Stimulants”[Mesh] OR “Amphetamines”[Mesh] OR Sedatives OR “Hypnotics and Sedatives”[Mesh] OR Benzodiazepines OR “Benzodiazepines”[Mesh] OR Anthramycin OR Bromazepam OR Clonazepam OR Devazepide OR Diazepam OR Flumazenil OR Flunitrazepam OR Flurazepam OR Fentanyl OR Alprazolam OR Clonidine OR Hashish Clonidine OR Lorazepam OR Nitrazepam OR Oxazepam OR Pirenzepine OR Prazepam OR Temazepam OR Chlordiazepoxide OR Clorazepate Dipotassium OR Estazolam OR Medazepam OR Midazolam OR Triazolam OR opioid* OR opiate* OR Heroin OR opium OR “Morphine Derivatives”[Mesh] OR Codeine OR Hydrocodone OR Oxycodone OR Dihydromorphine OR Ethylmorphine OR Heroin OR Hydromorphone OR Morphine OR Oxymorphone OR Thebaine OR Cocaine OR “Cocaine”[Mesh] OR Methamphetamine* OR “Methamphetamine”[Mesh] OR Benzphetamine OR anabolic steroids OR “Testosterone Congeners”[Mesh] OR antihistamines OR nitrous oxide OR betel nut OR kava OR Ecstasy OR phenylalkylamines OR mescaline OR 2,5-dimethoxy-4-methylamphetamine OR MDMA OR 3,4-methylenedioxymethamphetamine OR indoleamine* OR psilocybin OR psilocin OR dimethyltryptamine OR ergoline* OR lysergic acid diethylamide OR “morning glory seeds” OR “Salvia divinorum” OR jimsonweed OR anxiolytic OR benzodiazepine* OR zolpidem OR zaleplon OR carbamate* OR glutethimide OR meprobamate OR barbiturate* OR secobarbital OR barbiturate* OR glutethimide OR methaqualone OR amphetamine OR dextroamphetamine OR methamphetamine OR gabapentin OR baclofen OR diacetylmorphine OR kratom OR polydrug OR “poly-drug” OR polysubstance OR “poly-substance” OR “injection drug”) AND (addict* OR abus* OR misus* OR disorder* OR mis-use OR dependen*)) | 778,690
PubMed | 4 | ((#1) AND (#2)) AND (#3) | 9,423
PubMed | 5 | (#4) AND (1994:2024[pdat]) | 8,573
PubMed | 6 | (#5) NOT (child[MH] NOT adult[MH]) | 4,877
PubMed | 7 | (#6) NOT (“address”[pt] OR “autobiography”[pt] OR “bibliography”[pt] OR “biography”[pt] OR “case reports”[pt] OR “comment”[pt] OR “congress”[pt] OR “dictionary”[pt] OR “directory”[pt] OR “festschrift”[pt] OR “government publication”[pt] OR “historical article”[pt] OR “interview”[pt] OR “lecture”[pt] OR “legal case”[pt] OR “legislation”[pt] OR “news”[pt] OR “newspaper article”[pt] OR “patient education handout”[pt] OR “periodical index”[pt] OR “comment”[ti] OR “Editorial”[Publication Type] OR “ephemera”[pt] OR “in vitro techniques”[mh] OR “introductory journal article”[pt] OR (“Animals”[Mesh] NOT “Humans”[Mesh]) OR rats[tw] OR rat[tw] OR cow[tw] OR cows[tw] OR chicken*[tw] OR horse[tw] OR horses[tw] OR mice[tw] OR mouse[tw] OR bovine[tw] OR sheep[tw] OR ovine[tw] OR murinae[tw] OR cats[tw] OR cat[tw] OR dog[tw] OR dogs[tw] OR rodent[tw]) | 3,255
PubMed | 8 | (#6) NOT (“address”[pt] OR “autobiography”[pt] OR “bibliography”[pt] OR “biography”[pt] OR “case reports”[pt] OR “comment”[pt] OR “congress”[pt] OR “dictionary”[pt] OR “directory”[pt] OR “festschrift”[pt] OR “government publication”[pt] OR “historical article”[pt] OR “interview”[pt] OR “lecture”[pt] OR “legal case”[pt] OR “legislation”[pt] OR “news”[pt] OR “newspaper article”[pt] OR “patient education handout”[pt] OR “periodical index”[pt] OR “comment”[ti] OR “Editorial”[Publication Type] OR “ephemera”[pt] OR “in vitro techniques”[mh] OR “introductory journal article”[pt] OR (“Animals”[Mesh] NOT “Humans”[Mesh]) OR rats[tw] OR rat[tw] OR cow[tw] OR cows[tw] OR chicken*[tw] OR horse[tw] OR horses[tw] OR mice[tw] OR mouse[tw] OR bovine[tw] OR sheep[tw] OR ovine[tw] OR murinae[tw] OR cats[tw] OR cat[tw] OR dog[tw] OR dogs[tw] OR rodent[tw]); Limits: Humans | 2,813
PubMed | 9 | (#6) NOT (“address”[pt] OR “autobiography”[pt] OR “bibliography”[pt] OR “biography”[pt] OR “case reports”[pt] OR “comment”[pt] OR “congress”[pt] OR “dictionary”[pt] OR “directory”[pt] OR “festschrift”[pt] OR “government publication”[pt] OR “historical article”[pt] OR “interview”[pt] OR “lecture”[pt] OR “legal case”[pt] OR “legislation”[pt] OR “news”[pt] OR “newspaper article”[pt] OR “patient education handout”[pt] OR “periodical index”[pt] OR “comment”[ti] OR “Editorial”[Publication Type] OR “ephemera”[pt] OR “in vitro techniques”[mh] OR “introductory journal article”[pt] OR (“Animals”[Mesh] NOT “Humans”[Mesh]) OR rats[tw] OR rat[tw] OR cow[tw] OR cows[tw] OR chicken*[tw] OR horse[tw] OR horses[tw] OR mice[tw] OR mouse[tw] OR bovine[tw] OR sheep[tw] OR ovine[tw] OR murinae[tw] OR cats[tw] OR cat[tw] OR dog[tw] OR dogs[tw] OR rodent[tw]); Limits: Humans, English | 2,656
EMBASE | 1 | (“Attention Deficit Disorder with Hyperactivity” or “attention deficit hyperactivity disorder” or “ADHD” or “attention deficit disorder” or “ADDH” or “attention disorder” or “hyperactive disorder”).mp. [mp=title, abstract, heading word, drug trade name, original title, device manufacturer, drug manufacturer, device trade name, keyword heading word, floating subheading word, candidate term word] | 86674
EMBASE | 2 | (“Attention Deficit Disorder with Hyperactivity/drug therapy” or “Central Nervous System Stimulants” or “Methylphenidate” or “Dexmethylphenidate” or “Dextroamphetamine” or “Adderall” or “lisdexamfetamine dimesylate” or “Amphetamine” or “psychostimulant” or “Methylphenidate” or “Methylphenidate Hydrochloride” or “Aptensio” or “Concerta” or “Ritalin” or “Ritalin LA” or “Medikinet” or “Equasym” or “Quillivant” or “Metadate” or “Daytrana” or “Focalin” or “Dexedrine” or “Dextrostat” or “ProCentra” or “Zenzedi” or “mixed amphetamine salts” or “lisdexamfetamine” or “Vyvanse” or “Venvanse” or “Elvanse” or “Tyvense” or “Dyanavel” or “Evekeo” or “ADHD medications” or “Adzenys” or “Amfetamine” or “amfetamine aspartate” or “amphetamine aspartate” or “Amphetamines” or “Apo-methylphenidate” or “Apo-MPH” or “Attenta” or “Biphentin” or “dexamfetamine” or “dexamphetamine” or “Dexmethylphenidate” or “dextroamfetamine” or “lisdexamphetamine” or “Methamphetamine” or “methylfenidate” or “Methylin” or “QuilliChew” or “Stimulant”).mp. [mp=title, abstract, heading word, drug trade name, original title, device manufacturer, drug manufacturer, device trade name, keyword heading word, floating subheading word, candidate term word] | 125585
EMBASE | 3 | (“Substance-Related Disorders” or “Drug abuse” or “drug misuse” or “drug dependence” or “drug addiction” or “substance use disorder” or “substance abuse” or “substance misuse” or “substance dependence” or “substance addiction” or “prescription abuse” or “Alcoholism” or “cannabis use disorder” or “alcohol use disorder” or “stimulant use disorder” or “hallucinogen use disorder” or “opioid use disorder” or “inhalant use disorder” or “diversion” or “illicit drug use” or “illegal drug use” or “problem substance use” or “problematic substance use” or “risky substance use” or “substance use consequences” or ((Alcohol or “Alcoholic Beverages” or cannabis or Marijuana or “Cannabis” or “Marijuana Abuse” or “Marijuana Smoking” or opioids or “Narcotics” or “Analgesics, Opioid” or kratom or hallucinogens or “Psychotropic Drugs” or inhalants or toluene or stimulants or “Central Nervous System Stimulants” or “Amphetamines” or Sedatives or “Hypnotics and Sedatives” or Benzodiazepines or “Benzodiazepines” or Anthramycin or Bromazepam or Clonazepam or Devazepide or Diazepam or Flumazenil or Flunitrazepam or Flurazepam or Fentanyl or Alprazolam or Clonidine or Hashish Clonidine or Lorazepam or Nitrazepam or Oxazepam or Pirenzepine or Prazepam or Temazepam or Chlordiazepoxide or Clorazepate Dipotassium or Estazolam or Medazepam or Midazolam or Triazolam or opioid* or opiate* or Heroin or opium or “Morphine Derivatives” or Codeine or Hydrocodone or Oxycodone or Dihydromorphine or Ethylmorphine or Heroin or Hydromorphone or Morphine or Oxymorphone or Thebaine or Cocaine or “Cocaine” or Methamphetamine* or “Methamphetamine” or Benzphetamine or anabolic steroids or “Testosterone Congeners” or antihistamines or nitrous oxide or betel nut or kava or Ecstasy or phenylalkylamines or mescaline or 2,5-dimethoxy-4-methylamphetamine or MDMA or 3,4-methylenedioxymethamphetamine or indoleamine* or psilocybin or psilocin or dimethyltryptamine or ergoline* or lysergic acid diethylamide or “morning glory seeds” or “Salvia divinorum” or jimsonweed or anxiolytic or benzodiazepine* or zolpidem or zaleplon or carbamate* or glutethimide or meprobamate or barbiturate* or secobarbital or barbiturate* or glutethimide or methaqualone or amphetamine or dextroamphetamine or methamphetamine or gabapentin or baclofen or diacetylmorphine or kratom or polydrug or “poly-drug” or polysubstance or “poly-substance” or “injection drug”) and (addict* or abus* or misus* or disorder* or mis-use or dependen*))).mp. [mp=title, abstract, heading word, drug trade name, original title, device manufacturer, drug manufacturer, device trade name, keyword heading word, floating subheading word, candidate term word] | 758206
EMBASE | 4 | 1 and 2 and 3 | 9371
EMBASE | 5 | child/ | 2135811
EMBASE | 6 | adult/ | 9406839
EMBASE | 7 | 5 not 6 | 1451340
EMBASE | 8 | 4 not 7 | 7228
EMBASE | 9 | limit 8 to (human and yr=“1994 -Current” and (article or article in press) and “humans only (removes records about animals)”) | 2850
EMBASE | 10 | limit 9 to english language | 2729
EMBASE | 11 | limit 10 to english language | 2729
PsycINFO | 1 | MA ( “Attention Deficit Disorder with Hyperactivity” or “attention deficit hyperactivity disorder” or “ADHD” or “attention deficit disorder” or “ADDH” or “attention disorder” or “hyperactive disorder” ) OR TI ( “Attention Deficit Disorder with Hyperactivity” or “attention deficit hyperactivity disorder” or “ADHD” or “attention deficit disorder” or “ADDH” or “attention disorder” or “hyperactive disorder” ) OR AB ( “Attention Deficit Disorder with Hyperactivity” or “attention deficit hyperactivity disorder” or “ADHD” or “attention deficit disorder” or “ADDH” or “attention disorder” or “hyperactive disorder” ) | 41656
PsycINFO | 2 | MA ( “Attention Deficit Disorder with Hyperactivity/drug therapy” or “Central Nervous System Stimulants” or “Methylphenidate” or “Dexmethylphenidate” or “Dextroamphetamine” or “Adderall” or “lisdexamfetamine dimesylate” or “Amphetamine” or “psychostimulant” or “Methylphenidate” or “Methylphenidate Hydrochloride” or “Aptensio” or “Concerta” or “Ritalin” or “Ritalin LA” or “Medikinet” or “Equasym” or “Quillivant” or “Metadate” or “Daytrana” or “Focalin” or “Dexedrine” or “Dextrostat” or “ProCentra” or “Zenzedi” or “mixed amphetamine salts” or “lisdexamfetamine” or “Vyvanse” or “Venvanse” or “Elvanse” or “Tyvense” or “Dyanavel” or “Evekeo” or “ADHD medications” or “Adzenys” or “Amfetamine” or “amfetamine aspartate” or “amphetamine aspartate” or “Amphetamines” or “Apo-methylphenidate” or “Apo-MPH” or “Attenta” or “Biphentin” or “dexamfetamine” or “dexamphetamine” or “Dexmethylphenidate” or “dextroamfetamine” or “lisdexamphetamine” or “Methamphetamine” or “methylfenidate” or “Methylin” or “QuilliChew” or “Stimulant” ) OR TI ( “Attention Deficit Disorder with Hyperactivity/drug therapy” or “Central Nervous System Stimulants” or “Methylphenidate” or “Dexmethylphenidate” or “Dextroamphetamine” or “Adderall” or “lisdexamfetamine dimesylate” or “Amphetamine” or “psychostimulant” or “Methylphenidate” or “Methylphenidate Hydrochloride” or “Aptensio” or “Concerta” or “Ritalin” or “Ritalin LA” or “Medikinet” or “Equasym” or “Quillivant” or “Metadate” or “Daytrana” or “Focalin” or “Dexedrine” or “Dextrostat” or “ProCentra” or “Zenzedi” or “mixed amphetamine salts” or “lisdexamfetamine” or “Vyvanse” or “Venvanse” or “Elvanse” or “Tyvense” or “Dyanavel” or “Evekeo” or “ADHD medications” or “Adzenys” or “Amfetamine” or “amfetamine aspartate” or “amphetamine aspartate” or “Amphetamines” or “Apo-methylphenidate” or “Apo-MPH” or “Attenta” or “Biphentin” or “dexamfetamine” or “dexamphetamine” or “Dexmethylphenidate” or “dextroamfetamine” or “lisdexamphetamine” or “Methamphetamine” or “methylfenidate” or “Methylin” or “QuilliChew” or “Stimulant” ) OR AB ( “Attention Deficit Disorder with Hyperactivity/drug therapy” or “Central Nervous System Stimulants” or “Methylphenidate” or “Dexmethylphenidate” or “Dextroamphetamine” or “Adderall” or “lisdexamfetamine dimesylate” or “Amphetamine” or “psychostimulant” or “Methylphenidate” or “Methylphenidate Hydrochloride” or “Aptensio” or “Concerta” or “Ritalin” or “Ritalin LA” or “Medikinet” or “Equasym” or “Quillivant” or “Metadate” or “Daytrana” or “Focalin” or “Dexedrine” or “Dextrostat” or “ProCentra” or “Zenzedi” or “mixed amphetamine salts” or “lisdexamfetamine” or “Vyvanse” or “Venvanse” or “Elvanse” or “Tyvense” or “Dyanavel” or “Evekeo” or “ADHD medications” or “Adzenys” or “Amfetamine” or “amfetamine aspartate” or “amphetamine aspartate” or “Amphetamines” or “Apo-methylphenidate” or “Apo-MPH” or “Attenta” or “Biphentin” or “dexamfetamine” or “dexamphetamine” or “Dexmethylphenidate” or “dextroamfetamine” or “lisdexamphetamine” or “Methamphetamine” or “methylfenidate” or “Methylin” or “QuilliChew” or “Stimulant” ) | 34708
PsycINFO | 3 | MA ( “Substance-Related Disorders” or “Drug abuse” or “drug misuse” or “drug dependence” or “drug addiction” or “substance use disorder” or “substance abuse” or “substance misuse” or “substance dependence” or “substance addiction” or “prescription abuse” or “Alcoholism” or “cannabis use disorder” or “alcohol use disorder” or “stimulant use disorder” or “hallucinogen use disorder” or “opioid use disorder” or “inhalant use disorder” or “diversion” or “illicit drug use” or “illegal drug use” or “problem substance use” or “problematic substance use” or “risky substance use” or “substance use consequences” or ((Alcohol or “Alcoholic Beverages” or cannabis or Marijuana or “Cannabis” or “Marijuana Abuse” or “Marijuana Smoking” or opioids or “Narcotics” or “Analgesics, Opioid” or kratom or hallucinogens or “Psychotropic Drugs” or inhalants or toluene or stimulants or “Central Nervous System Stimulants” or “Amphetamines” or Sedatives or “Hypnotics and Sedatives” or Benzodiazepines or “Benzodiazepines” or Anthramycin or Bromazepam or Clonazepam or Devazepide or Diazepam or Flumazenil or Flunitrazepam or Flurazepam or Fentanyl or Alprazolam or Clonidine or Hashish Clonidine or Lorazepam or Nitrazepam or Oxazepam or Pirenzepine or Prazepam or Temazepam or Chlordiazepoxide or Clorazepate Dipotassium or Estazolam or Medazepam or Midazolam or Triazolam or opioid* or opiate* or Heroin or opium or “Morphine Derivatives” or Codeine or Hydrocodone or Oxycodone or Dihydromorphine or Ethylmorphine or Heroin or Hydromorphone or Morphine or Oxymorphone or Thebaine or Cocaine or “Cocaine” or Methamphetamine* or “Methamphetamine” or Benzphetamine or anabolic steroids or “Testosterone Congeners” or antihistamines or nitrous oxide or betel nut or kava or Ecstasy or phenylalkylamines or mescaline or 2,5-dimethoxy-4-methylamphetamine or MDMA or 3,4-methylenedioxymethamphetamine or indoleamine* or psilocybin or psilocin or dimethyltryptamine or ergoline* or lysergic acid diethylamide or “morning glory seeds” or “Salvia divinorum” or jimsonweed or anxiolytic or benzodiazepine* or zolpidem or zaleplon or carbamate* or glutethimide or meprobamate or barbiturate* or secobarbital or barbiturate* or glutethimide or methaqualone or amphetamine or dextroamphetamine or methamphetamine or gabapentin or baclofen or diacetylmorphine or kratom or polydrug or “poly-drug” or polysubstance or “poly-substance” or “injection drug”) and (addict* or abus* or misus* or disorder* or mis-use or dependen*))) OR TI ( “Substance-Related Disorders” or “Drug abuse” or “drug misuse” or “drug dependence” or “drug addiction” or “substance use disorder” or “substance abuse” or “substance misuse” or “substance dependence” or “substance addiction” or “prescription abuse” or “Alcoholism” or “cannabis use disorder” or “alcohol use disorder” or “stimulant use disorder” or “hallucinogen use disorder” or “opioid use disorder” or “inhalant use disorder” or “diversion” or “illicit drug use” or “illegal drug use” or “problem substance use” or “problematic substance use” or “risky substance use” or “substance use consequences” or ((Alcohol or “Alcoholic Beverages” or cannabis or Marijuana or “Cannabis” or “Marijuana Abuse” or “Marijuana Smoking” or opioids or “Narcotics” or “Analgesics, Opioid” or kratom or hallucinogens or “Psychotropic Drugs” or inhalants or toluene or stimulants or “Central Nervous System Stimulants” or “Amphetamines” or Sedatives or “Hypnotics and Sedatives” or Benzodiazepines or “Benzodiazepines” or Anthramycin or Bromazepam or Clonazepam or Devazepide or Diazepam or Flumazenil or Flunitrazepam or Flurazepam or Fentanyl or Alprazolam or Clonidine or Hashish Clonidine or Lorazepam or Nitrazepam or Oxazepam or Pirenzepine or Prazepam or Temazepam or Chlordiazepoxide or Clorazepate Dipotassium or Estazolam or Medazepam or Midazolam or Triazolam or opioid* or opiate* or Heroin or opium or “Morphine Derivatives” or Codeine or Hydrocodone or Oxycodone or Dihydromorphine or Ethylmorphine or Heroin or Hydromorphone or Morphine or Oxymorphone or Thebaine or Cocaine or “Cocaine” or Methamphetamine* or “Methamphetamine” or Benzphetamine or anabolic steroids or “Testosterone Congeners” or antihistamines or nitrous oxide or betel nut or kava or Ecstasy or phenylalkylamines or mescaline or 2,5-dimethoxy-4-methylamphetamine or MDMA or 3,4-methylenedioxymethamphetamine or indoleamine* or psilocybin or psilocin or dimethyltryptamine or ergoline* or lysergic acid diethylamide or “morning glory seeds” or “Salvia divinorum” or jimsonweed or anxiolytic or benzodiazepine* or zolpidem or zaleplon or carbamate* or glutethimide or meprobamate or barbiturate* or secobarbital or barbiturate* or glutethimide or methaqualone or amphetamine or dextroamphetamine or methamphetamine or gabapentin or baclofen or diacetylmorphine or kratom or polydrug or “poly-drug” or polysubstance or “poly-substance” or “injection drug”) and (addict* or abus* or misus* or disorder* or mis-use or dependen*))) OR AB ( “Substance-Related Disorders” or “Drug abuse” or “drug misuse” or “drug dependence” or “drug addiction” or “substance use disorder” or “substance abuse” or “substance misuse” or “substance dependence” or “substance addiction” or “prescription abuse” or “Alcoholism” or “cannabis use disorder” or “alcohol use disorder” or “stimulant use disorder” or “hallucinogen use disorder” or “opioid use disorder” or “inhalant use disorder” or “diversion” or “illicit drug use” or “illegal drug use” or “problem substance use” or “problematic substance use” or “risky substance use” or “substance use consequences” or ((Alcohol or “Alcoholic Beverages” or cannabis or Marijuana or “Cannabis” or “Marijuana Abuse” or “Marijuana Smoking” or opioids or “Narcotics” or “Analgesics, Opioid” or kratom or hallucinogens or “Psychotropic Drugs” or inhalants or toluene or stimulants or “Central Nervous System Stimulants” or “Amphetamines” or Sedatives or “Hypnotics and Sedatives” or Benzodiazepines or “Benzodiazepines” or Anthramycin or Bromazepam or Clonazepam or Devazepide or Diazepam or Flumazenil or Flunitrazepam or Flurazepam or Fentanyl or Alprazolam or Clonidine or Hashish Clonidine or Lorazepam or Nitrazepam or Oxazepam or Pirenzepine or Prazepam or Temazepam or Chlordiazepoxide or Clorazepate Dipotassium or Estazolam or Medazepam or Midazolam or Triazolam or opioid* or opiate* or Heroin or opium or “Morphine Derivatives” or Codeine or Hydrocodone or Oxycodone or Dihydromorphine or Ethylmorphine or Heroin or Hydromorphone or Morphine or Oxymorphone or Thebaine or Cocaine or “Cocaine” or Methamphetamine* or “Methamphetamine” or Benzphetamine or anabolic steroids or “Testosterone Congeners” or antihistamines or nitrous oxide or betel nut or kava or Ecstasy or phenylalkylamines or mescaline or 2,5-dimethoxy-4-methylamphetamine or MDMA or 3,4-methylenedioxymethamphetamine or indoleamine* or psilocybin or psilocin or dimethyltryptamine or ergoline* or lysergic acid diethylamide or “morning glory seeds” or “Salvia divinorum” or jimsonweed or anxiolytic or benzodiazepine* or zolpidem or zaleplon or carbamate* or glutethimide or meprobamate or barbiturate* or secobarbital or barbiturate* or glutethimide or methaqualone or amphetamine or dextroamphetamine or methamphetamine or gabapentin or baclofen or diacetylmorphine or kratom or polydrug or “poly-drug” or polysubstance or “poly-substance” or “injection drug”) and (addict* or abus* or misus* or disorder* or mis-use or dependen*))) | 226471
PsycINFO | 4 | s1 AND s2 AND s3 | 4608
PsycINFO | 5 | s4 NOT ( childhood[AG] NOT adulthood[AG] ) | 4608
PsycINFO | 6 | s5 (Limiters - Methodology: BRAIN IMAGING, CLINICAL TRIAL, EMPIRICAL STUDY, -Experimental Replication, -Followup Study, - Longitudinal Study, ---Prospective Study, ---Retrospective Study, FIELD STUDY, -Systematic Review, META ANALYSIS, METASYNTHESIS, QUANTITATIVE STUDY, TREATMENT OUTCOME, TWIN STUDY) | 3062
PsycINFO | 7 | s6 (Limiters - Publication Year: 1994-2024; Peer Reviewed; Publication Type: Peer Reviewed Journal; Population Group: Human; Document Type: Journal Article) | 2353
PsycINFO | 8 | s7 (Limiters - English language) | 2302
Cochrane Library | 1 | Attention Deficit Disorder with Hyperactivity or “attention deficit hyperactivity disorder” or “ADHD” or “attention deficit disorder” or “ADDH” or “attention disorder” or “hyperactive disorder” | 7648
Cochrane Library | 2 | Attention Deficit Disorder with Hyperactivity drug therapy or “Central Nervous System Stimulants” or “Methylphenidate” or “Dexmethylphenidate” or “Dextroamphetamine” or “Adderall” or “lisdexamfetamine dimesylate” or “Amphetamine” or “psychostimulant” or “Methylphenidate” or “Methylphenidate Hydrochloride” or “Aptensio” or “Concerta” or “Ritalin” or “Ritalin LA” or “Medikinet” or “Equasym” or “Quillivant” or “Metadate” or “Daytrana” or “Focalin” or “Dexedrine” or “Dextrostat” or “ProCentra” or “Zenzedi” or “mixed amphetamine salts” or “lisdexamfetamine” or “Vyvanse” or “Venvanse” or “Elvanse” or “Tyvense” or “Dyanavel” or “Evekeo” or “ADHD medications” or “Adzenys” or “Amfetamine” or “amfetamine aspartate” or “amphetamine aspartate” or “Amphetamines” or “Apo-methylphenidate” or “Apo-MPH” or “Attenta” or “Biphentin” or “dexamfetamine” or “dexamphetamine” or “Dexmethylphenidate” or “dextroamfetamine” or “lisdexamphetamine” or “Methamphetamine” or “methylfenidate” or “Methylin” or “QuilliChew” or “Stimulant” | 10547
Cochrane Library | 3 | Substance-Related Disorders or “Drug abuse” or “drug misuse” or “drug dependence” or “drug addiction” or “substance use disorder” or “substance abuse” or “substance misuse” or “substance dependence” or “substance addiction” or “prescription abuse” or “Alcoholism” or “cannabis use disorder” or “alcohol use disorder” or “stimulant use disorder” or “hallucinogen use disorder” or “opioid use disorder” or “inhalant use disorder” or “diversion” or “illicit drug use” or “illegal drug use” or “problem substance use” or “problematic substance use” or “risky substance use” or “substance use consequences” or addict* or abus* or misus* or mis-use or dependen* | 128415
Cochrane Library | 4 | #1 AND #2 AND #3 | 569
CT.gov | 1 | (Attention Deficit Disorder with Hyperactivity OR “attention deficit hyperactivity disorder” OR “ADHD” OR “attention deficit disorder” OR “ADDH” OR “attention disorder” OR “hyperactive disorder”) AND (“Central Nervous System Stimulants” OR “Methylphenidate” OR “Dexmethylphenidate” OR “Dextroamphetamine” OR “Adderall” OR “lisdexamfetamine dimesylate” OR “Amphetamine” OR “psychostimulant” OR “Methylphenidate” OR “Methylphenidate Hydrochloride” OR “Aptensio” OR “Concerta” OR “Ritalin” OR “Ritalin LA” OR “Medikinet” OR “Equasym” OR “Quillivant” OR “Metadate” OR “Daytrana” OR “Focalin” OR “Dexedrine” OR “Dextrostat” OR “ProCentra” OR “Zenzedi” OR “mixed amphetamine salts” OR “lisdexamfetamine” OR “Vyvanse” OR “Venvanse” OR “Elvanse” OR “Tyvense” OR “Dyanavel” OR “Evekeo” OR “ADHD medications” OR “Adzenys” OR “Amfetamine” OR “amfetamine aspartate” OR “amphetamine aspartate” OR “Amphetamines” OR “Apo-methylphenidate” OR “Apo-MPH” OR “Attenta” OR “Biphentin” OR “dexamfetamine” OR “dexamphetamine” OR “Dexmethylphenidate” OR “dextroamfetamine” OR “lisdexamphetamine” OR “Methamphetamine” OR “methylfenidate” OR “Methylin” OR “QuilliChew” OR “Stimulant”) AND (Substance-Related Disorders OR “Drug abuse” OR “drug misuse” OR “drug dependence” OR “drug addiction” OR “substance use disorder” OR “substance abuse” OR “substance misuse” OR “substance dependence” OR “substance addiction” OR “prescription abuse” OR “Alcoholism” OR “cannabis use disorder” OR “alcohol use disorder” OR “stimulant use disorder” OR “hallucinogen use disorder” OR “opioid use disorder” OR “inhalant use disorder” OR “diversion” OR “illicit drug use” OR “illegal drug use” OR “problem substance use” OR “problematic substance use” OR “risky substance use” OR “substance use consequences” OR addict* OR abus* OR misus* OR mis-use OR dependen*) | 23
| | Total | 8,280
| | Total after deduplication | 6419