# ABBREVIATIONS TABLE

Abbreviation: Definition
AARS: Adult ADHD Rating Scale
ADHD: Attention-deficit/hyperactivity disorder
aHR: Adjusted hazard ratio
AISRS: Adult ADHD Investigator Symptom Rating Scale
AUD: Alcohol use disorder
CAARS: Conners Adult ADHD Rating Scales
CBT: Cognitive behavioral therapy
CGI: Clinical Global Improvement Scale
DSM: Diagnostic and Statistical Manual of Mental Disorders
GRADE: Grading of Recommendations Assessment, Development and Evaluation
ICD: International classification of disease
KQ: Key question
M: Mean
MD: Mean difference
MeSH: Medical subject headings
N: Number
NRCS: Non-randomized comparative studies
OMHSP: Office of Mental Health and Suicide Prevention
OR: Odds ratio
RCT: Randomized controlled trial
SD: Standard deviation
SRDR+: Systematic Review Data Repository
SUD: Substance use disorders
TAADDS: Targeted Adult Attention Deficit Disorder Scale
TEP: Technical expert panel
THC: Tetrahydrocannabinol
VA: US Department of Veterans Affairs
VHA: Veterans Health Administration