# REFERENCES

1 Unschuld P, Andrews B. Traditional Chinese Medicine. Columbia University Press; 2018.
2 National Center for Complementary and Integrative Health. Acupuncture: In Depth. 2015. https://www.nccih.nih.gov/health/acupuncture-in-depth
3 Li Y. Acupuncture journey to America: A turning point in 1971. Vol. Journal of Traditional Chinese Medical Sciences. 2015.
4 Institute of Medicine (US) Committee on the Use of Complementary and Alternative Medicine by the American Public. Complementary and Alternative Medicine in the United States. 2005. https://www.ncbi.nlm.nih.gov/books/NBK83804/
5 Department of Veterans Affairs. Provision of Complementary and Integrative Health. 2017.
6 Hempel S, Taylor, S. L., Solloway, M., Miake-Lye, I. M., Beroes, J. M., Shanman, R., Booth, M. J., Siroka, A. M., Shekelle, P. G. Evidence Map of Acupuncture. Vol. VA-ESP Project #05-226. 2013. https://www.ncbi.nlm.nih.gov/books/NBK185072/
7 GRADE Working Group. gradeworkinggroup.org. Accessed 2022.
8 Berkman ND, Lohr KN, Ansari MT, . Grading the strength of a body of evidence when assessing health care interventions: an EPC update. J Clin Epidemiol. Nov 2015;68(11):1312–24. doi:10.1016/j.jclinepi.2014.11.023 25721570
9 Franco JVA, Turk T, Jung JH, . Non-pharmacological interventions for treating chronic prostatitis/chronic pelvic pain syndrome: a Cochrane systematic review. BJU Int. Aug 2019;124(2):197–208. doi:10.1111/bju.14492 30019814
10 Chou R, Deyo R, Friedly J, . Nonpharmacologic Therapies for Low Back Pain: A Systematic Review for an American College of Physicians Clinical Practice Guideline. Ann Intern Med. Apr 4 2017;166(7):493–505. doi:10.7326/m16-2459 28192793
11 Wang YY, Li XX, Liu JP, Luo H, Ma LX, Alraek T. Traditional Chinese medicine for chronic fatigue syndrome: a systematic review of randomized clinical trials. Complement Ther Med. Aug 2014;22(4):826–33. doi:10.1016/j.ctim.2014.06.004 25146086
12 Liu S, Zhang CS, Cai Y, . Acupuncture for Post-stroke Shoulder-Hand Syndrome: A Systematic Review and Meta-Analysis. Front Neurol. 2019;10:433. doi:10.3389/fneur.2019.00433 31105643
13 Chia KL, Lam RPK, Lam CK, Tsui SH. Acupuncture in the emergency department: a systematic review of randomised controlled trials. Acupunct Med. Jun 2018;36(3):183–192. doi:10.1136/acupmed-2017-011547 29581138
14 Navarro-Santana MJ, Sanchez-Infante J, Gómez-Chiguano GF, Cummings M, Fernández-de-Las-Peñas C, Plaza-Manzano G. Effects of manual acupuncture and electroacupuncture for lateral epicondylalgia of musculoskeletal origin: a systematic review and meta-analysis. Acupunct Med. Dec 17 2020:964528420967364. doi:10.1177/0964528420967364
15 Savage J, Waddell A. Tinnitus. BMJ Clin Evid. Oct 20 2014;2014
16 Vickers AJ, Vertosick EA, Lewith G, . Acupuncture for Chronic Pain: Update of an Individual Patient Data Meta-Analysis. J Pain. May 2018;19(5):455–474. doi:10.1016/j.jpain.2017.11.005 29198932
17 Choi GH, Wieland LS, Lee H, Sim H, Lee MS, Shin BC. Acupuncture and related interventions for the treatment of symptoms associated with carpal tunnel syndrome. Cochrane Database Syst Rev. Dec 2 2018;12(12):Cd011215. doi:10.1002/14651858.CD011215.pub2 30521680
18 Eccleston C, Fisher E, Thomas KH, . Interventions for the reduction of prescribed opioid use in chronic non-cancer pain. Cochrane Database Syst Rev. Nov 13 2017;11(11):Cd010323. doi:10.1002/14651858.CD010323.pub3 29130474
19 Chou R, Wagner J, Ahmed AY, . AHRQ Comparative Effectiveness Reviews. Treatments for Acute Pain: A Systematic Review. Agency for Healthcare Research and Quality (US); 2020.
20 Skelly AC, Chou R, Dettori JR, . AHRQ Comparative Effectiveness Reviews. Noninvasive Nonpharmacological Treatment for Chronic Pain: A Systematic Review Update. Agency for Healthcare Research and Quality (US); 2020.
21 Yuan QL, Wang P, Liu L, . Acupuncture for musculoskeletal pain: A meta-analysis and meta-regression of sham-controlled randomized clinical trials. Sci Rep. Jul 29 2016;6:30675. doi:10.1038/srep30675 27471137
22 Yuanqing P, Yong T, Haiqian L, . Acupuncture for Hormone Therapy-Related Side Effects in Breast Cancer Patients: A GRADE-Assessed Systematic Review and Updated Meta-Analysis. Integr Cancer Ther. Jan–Dec 2020;19:1534735420940394. doi:10.1177/1534735420940394 32718258
23 Hwang MS, Lee HY, Choi TY, . A systematic review and meta-analysis of the efficacy of acupuncture and electroacupuncture against chemotherapy-induced peripheral neuropathy. Medicine (Baltimore). Apr 2020;99(17):e19837. doi:10.1097/md.0000000000019837 32332632
24 Hu C, Zhang H, Wu W, . Acupuncture for Pain Management in Cancer: A Systematic Review and Meta-Analysis. Evid Based Complement Alternat Med. 2016;2016:1720239. doi:10.1155/2016/1720239 26977172
25 Amato Nesbit S, Sharma R, Waldfogel JM, . Non-pharmacologic treatments for symptoms of diabetic peripheral neuropathy: a systematic review. Curr Med Res Opin. Jan 2019;35(1):15–25. doi:10.1080/03007995.2018.1497958 30114983
26 Kim J, Kim SR, Lee H, Nam DH. Comparing Verum and Sham Acupuncture in Fibromyalgia Syndrome: A Systematic Review and Meta-Analysis. Evid Based Complement Alternat Med. 2019;2019:8757685. doi:10.1155/2019/8757685 31534469
27 Zhang XC, Chen H, Xu WT, Song YY, Gu YH, Ni GX. Acupuncture therapy for fibromyalgia: a systematic review and meta-analysis of randomized controlled trials. J Pain Res. 2019;12:527–542. doi:10.2147/jpr.S186227 30787631
28 Giovanardi CM, Cinquini M, Aguggia M, . Acupuncture vs. Pharmacological Prophylaxis of Migraine: A Systematic Review of Randomized Controlled Trials. Front Neurol. 2020;11:576272. doi:10.3389/fneur.2020.576272 33391147
29 Yun JM, Lee SH, Cho JH, Kim KW, Ha IH. The effects of acupuncture on occipital neuralgia: a systematic review and meta-analysis. BMC Complement Med Ther. Jun 3 2020;20(1):171. doi:10.1186/s12906-020-02955-y 32493452
30 Xu J, Zhang FQ, Pei J, Ji J. Acupuncture for migraine without aura: a systematic review and meta-analysis. J Integr Med. Sep 2018;16(5):312–321. doi:10.1016/j.joim.2018.06.002 30007828
31 Linde K, Allais G, Brinkhaus B, . Acupuncture for the prevention of episodic migraine. Cochrane Database Syst Rev. Jun 28 2016;2016(6):Cd001218. doi:10.1002/14651858.CD001218.pub3 27351677
32 Linde K, Allais G, Brinkhaus B, . Acupuncture for the prevention of tension-type headache. Cochrane Database Syst Rev. Apr 19 2016;4:Cd007587. doi:10.1002/14651858.CD007587.pub2 27092807
33 Ju ZY, Wang K, Cui HS, . Acupuncture for neuropathic pain in adults. Cochrane Database Syst Rev. Dec 2 2017;12(12):Cd012057. doi:10.1002/14651858.CD012057.pub2 29197180
34 Pei W, Zeng J, Lu L, Lin G, Ruan J. Is acupuncture an effective postherpetic neuralgia treatment? A systematic review and meta-analysis. J Pain Res. 2019;12:2155–2165. doi:10.2147/jpr.S199950 31410050
35 Zimpel SA, Torloni MR, Porfírio GJ, Flumignan RL, da Silva EM. Complementary and alternative therapies for post-caesarean pain. Cochrane Database Syst Rev. Sep 1 2020;9:Cd011216. doi:10.1002/14651858.CD011216.pub2 32871021
36 Yin Z, Xiao Q, Xu G, . Acupuncture for the Postcholecystectomy Syndrome: A Systematic Review and Meta-Analysis. Evid Based Complement Alternat Med. 2020;2020:7509481. doi:10.1155/2020/7509481 32802133
37 Tedesco D, Gori D, Desai KR, . Drug-Free Interventions to Reduce Pain or Opioid Consumption After Total Knee Arthroplasty: A Systematic Review and Meta-analysis. JAMA Surg. Oct 18 2017;152(10):e172872. doi:10.1001/jamasurg.2017.2872 28813550
38 Hu H, Chen L, Ma R, Gao H, Fang J. Acupuncture for primary trigeminal neuralgia: A systematic review and PRISMA-compliant meta-analysis. Complement Ther Clin Pract. Feb 2019;34:254–267. doi:10.1016/j.ctcp.2018.12.013 30712736
39 Kim TH, Lee MS, Kim KH, Kang JW, Choi TY, Ernst E. Acupuncture for treating acute ankle sprains in adults. Cochrane Database Syst Rev. Jun 23 2014;(6):Cd009065. doi:10.1002/14651858.CD009065.pub2 24953665
40 Tang S, Mo Z, Zhang R. Acupuncture for lumbar disc herniation: a systematic review and meta-analysis. Acupunct Med. Apr 2018;36(2):62–70. doi:10.1136/acupmed-2016-011332 29496679
41 Xiang A, Cheng K, Shen X, Xu P, Liu S. The Immediate Analgesic Effect of Acupuncture for Pain: A Systematic Review and Meta-Analysis. Evid Based Complement Alternat Med. 2017;2017:3837194. doi:10.1155/2017/3837194 29234385
42 Manheimer E, Cheng K, Wieland LS, . Acupuncture for hip osteoarthritis. Cochrane Database Syst Rev. May 5 2018;5(5):Cd013010. doi:10.1002/14651858.Cd013010 29729027
43 Ben-Arie E, Kao PY, Lee YC, Ho WC, Chou LW, Liu HP. The Effectiveness of Acupuncture in the Treatment of Frozen Shoulder: A Systematic Review and Meta-Analysis. Evid Based Complement Alternat Med. 2020;2020:9790470. doi:10.1155/2020/9790470 33062030
44 Tong QY, Liu R, Zhang K, Gao Y, Cui GW, Shen WD. Can acupuncture therapy reduce preoperative anxiety? A systematic review and meta-analysis. J Integr Med. Jan 2021;19(1):20–28. doi:10.1016/j.joim.2020.10.007 33288487
45 Liu R, Zhang K, Tong QY, Cui GW, Ma W, Shen WD. Acupuncture for post-stroke depression: a systematic review and meta-analysis. BMC Complement Med Ther. Apr 1 2021;21(1):109. doi:10.1186/s12906-021-03277-3 33794857
46 Smith CA, Shewamene Z, Galbally M, Schmied V, Dahlen H. The effect of complementary medicines and therapies on maternal anxiety and depression in pregnancy: A systematic review and meta-analysis. J Affect Disord. Feb 15 2019;245:428–439. doi:10.1016/j.jad.2018.11.054 30423471
47 Smith CA, Armour M, Lee MS, Wang LQ, Hay PJ. Acupuncture for depression. Cochrane Database Syst Rev. Mar 4 2018;3(3):Cd004046. doi:10.1002/14651858.CD004046.pub4 29502347
48 Sorbero ME, Reynolds K, Colaiaco B, . Acupuncture for Major Depressive Disorder: A Systematic Review. Rand Health Q. May 9 2016;5(4):7.
49 Kwon CY, Lee B, Cheong MJ, . Non-pharmacological Treatment for Elderly Individuals With Insomnia: A Systematic Review and Network Meta-Analysis. Front Psychiatry. 2020;11:608896. doi:10.3389/fpsyt.2020.608896 33584374
50 Cao HJ, Yu ML, Wang LQ, Fei YT, Xu H, Liu JP. Acupuncture for Primary Insomnia: An Updated Systematic Review of Randomized Controlled Trials. J Altern Complement Med. May 2019;25(5):451–474. doi:10.1089/acm.2018.0046 31013432
51 Grant S, Colaiaco B, Motala A, Shanman R, Sorbero M, Hempel S. Acupuncture for the Treatment of Adults with Posttraumatic Stress Disorder: A Systematic Review and Meta-Analysis. J Trauma Dissociation. Jan–Feb 2018;19(1):39–58. doi:10.1080/15299732.2017.1289493 28151093
52 Shen X, Xia J, Adams CE. Acupuncture for schizophrenia. Cochrane Database Syst Rev. Oct 20 2014;(10):Cd005475. doi:10.1002/14651858.CD005475.pub2 25330045
53 Chen Z, Wang Y, Wang R, Xie J, Ren Y. Efficacy of Acupuncture for Treating Opioid Use Disorder in Adults: A Systematic Review and Meta-Analysis. Evid Based Complement Alternat Med. 2018;2018:3724708. doi:10.1155/2018/3724708 30622598
54 White AR, Rampes H, Liu JP, Stead LF, Campbell J. Acupuncture and related interventions for smoking cessation. Cochrane Database Syst Rev. Jan 23 2014;2014(1):Cd000009. doi:10.1002/14651858.CD000009.pub4 24459016
55 Jo J, Lee YJ, Lee H. Effectiveness of Acupuncture for Primary Ovarian Insufficiency: A Systematic Review and Meta-Analysis. Evid Based Complement Alternat Med. 2015;2015:842180. doi:10.1155/2015/842180 26089949
56 Smith CA, Armour M, Zhu X, Li X, Lu ZY, Song J. Acupuncture for dysmenorrhoea. Cochrane Database Syst Rev. Apr 18 2016;4:Cd007854. doi:10.1002/14651858.CD007854.pub3 27087494
57 Coyle ME, Stupans I, Abdel-Nour K, . Acupuncture versus placebo acupuncture for in vitro fertilisation: a systematic review and meta-analysis. Acupunct Med. Feb 2021;39(1):20–29. doi:10.1177/0964528420958711 33040570
58 Lim CED, Ng RWC, Cheng NCL, Zhang GS, Chen H. Acupuncture for polycystic ovarian syndrome. Cochrane Database Syst Rev. Jul 2 2019;7(7):Cd007689. doi:10.1002/14651858.CD007689.pub4 31264709
59 Kwan I, Wang R, Pearce E, Bhattacharya S. Pain relief for women undergoing oocyte retrieval for assisted reproduction. Cochrane Database Syst Rev. May 15 2018;5(5):Cd004829. doi:10.1002/14651858.CD004829.pub4 29761478
60 Jo J, Lee YJ. Effectiveness of acupuncture in women with polycystic ovarian syndrome undergoing in vitro fertilisation or intracytoplasmic sperm injection: a systematic review and meta-analysis. Acupunct Med. Jun 2017;35(3):162–170. doi:10.1136/acupmed-2016-011163 28077366
61 Dodin S, Blanchet C, Marc I, . Acupuncture for menopausal hot flushes. Cochrane Database Syst Rev. Jul 30 2013;2013(7):Cd007410. doi:10.1002/14651858.CD007410.pub2 23897589
62 Armour M, Ee CC, Hao J, Wilson TM, Yao SS, Smith CA. Acupuncture and acupressure for premenstrual syndrome. Cochrane Database Syst Rev. Aug 14 2018;8(8):Cd005290. doi:10.1002/14651858.CD005290.pub2 30105749
63 Liddle SD, Pennick V. Interventions for preventing and treating low-back and pelvic pain during pregnancy. Cochrane Database Syst Rev. Sep 30 2015;2015(9):Cd001139. doi:10.1002/14651858.CD001139.pub4 26422811
64 Yang M, Sun M, Du T, . The efficacy of acupuncture for stable angina pectoris: A systematic review and meta-analysis. Eur J Prev Cardiol. Sep 17 2019:2047487319876761. doi:10.1177/2047487319876761 31529993
65 Lin WF, Zhong MF, Zhou QH, . Efficacy of complementary and integrative medicine on health-related quality of life in cancer patients: a systematic review and meta-analysis. Cancer Manag Res. 2019;11:6663–6680. doi:10.2147/cmar.S195935 31413628
66 Zhang Q, Gong J, Dong H, Xu S, Wang W, Huang G. Acupuncture for chronic fatigue syndrome: a systematic review and meta-analysis. Acupunct Med. Aug 2019;37(4):211–222. doi:10.1136/acupmed-2017-011582 31204859
67 Pang B, Jiang T, Du YH, . Acupuncture for Functional Dyspepsia: What Strength Does It Have? A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Evid Based Complement Alternat Med. 2016;2016:3862916. doi:10.1155/2016/3862916 28119758
68 Cui Y, Wang F, Li H, Zhang X, Zhao X, Wang D. Efficacy of Acupuncture for Herpes Zoster: A Systematic Review and Meta-Analysis. Complement Med Res. Apr 6 2021:1–10. Wirksamkeit von Akupunktur bei Herpes Zoster: Eine systematische Übersicht und Metaanalyse. doi:10.1159/000515138 33176297
69 Wang X, Zhao NQ, Sun YX, . Acupuncture for ulcerative colitis: a systematic review and meta-analysis of randomized clinical trials. BMC Complement Med Ther. Oct 14 2020;20(1):309. doi:10.1186/s12906-020-03101-4 33054760
70 Guo J, Xing X, Wu J, . Acupuncture for Adults with Diarrhea-Predominant Irritable Bowel Syndrome or Functional Diarrhea: A Systematic Review and Meta-Analysis. Neural Plast. 2020;2020:8892184. doi:10.1155/2020/8892184 33299403
71 Zhou L, Wang Y, Qiao J, Wang QM, Luo X. Acupuncture for Improving Cognitive Impairment After Stroke: A Meta-Analysis of Randomized Controlled Trials. Front Psychol. 2020;11:549265. doi:10.3389/fpsyg.2020.549265 33424671
72 Tang HY, Tang W, Yang F, Wu WW, Shen GM. Efficacy of acupuncture in the management of post-apoplectic aphasia: a systematic review and meta-analysis of randomized controlled trials. BMC Complement Altern Med. Oct 25 2019;19(1):282. doi:10.1186/s12906-019-2687-1 31653216
73 Chan MWC, Wu XY, Wu JCY, Wong SYS, Chung VCH. Safety of Acupuncture: Overview of Systematic Reviews. Sci Rep. Jun 13 2017;7(1):3369. doi:10.1038/s41598-017-03272-0 28611366
74 Tan JY, Molassiotis A, Wang T, Suen LK. Adverse events of auricular therapy: a systematic review. Evid Based Complement Alternat Med. 2014;2014:506758. doi:10.1155/2014/506758 25435890
75 Wu J, Hu Y, Zhu Y, Yin P, Litscher G, Xu S. Systematic Review of Adverse Effects: A Further Step towards Modernization of Acupuncture in China. Evid Based Complement Alternat Med. 2015;2015:432467. doi:10.1155/2015/432467 26339265
76 Kim TH, Lee MS, Birch S, Alraek T. Plausible Mechanism of Sham Acupuncture Based on Biomarkers: A Systematic Review of Randomized Controlled Trials. Front Neurosci. 2022;16:834112. doi:10.3389/fnins.2022.834112 35185461