# ACKNOWLEDGMENTS

The authors are grateful to the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Juli Olson, DC, DACM
  National Lead for Acupuncture
  Integrative Health Coordinating Center
  VHA Office of Patient Centered Care & Cultural Transformation
- Benjamin Kligler, MD, MPH
  Executive Director
  VHA Office of Patient Centered Care & Cultural Transformation

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix F for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.