# INTRODUCTION

## PURPOSE

The Evidence Synthesis Program (ESP) is responding to a request from the VHA Office of Patient Centered Care & Cultural Transformation, Integrative Health Coordinating Center to provide current evidence regarding use of acupuncture for adult health conditions of interest to VA. Findings from this review will be used by VA referring providers, site leadership, and policy makers to improve Veteran access to non-pharmacologic treatment approaches and improve outcomes for Veterans by utilizing evidence-based care pathways.

## BACKGROUND

Acupuncture is a technique that is part of a larger system of care often referred to as Traditional Chinese Medicine. The Huangdi Neijing, also known as the Yellow Emperor’s Inner Classic, dates to approximately the second century BCE and is one of the oldest known medical texts with references to acupuncture.^1^ Trained practitioners stimulate specific points on the body, commonly by inserting thin needles into the skin with the intention of restoring and balancing the qi or energy of the mind and body and promoting health.^2^ Acupuncture has continued to grow in popularity since a New York Times journalist wrote in 1971 about receiving acupuncture for pain after an emergency appendectomy, and the following year, the use of acupuncture in the surgical setting was observed during a Presidential visit to China.^3^

Multiple national surveys in the early 1990s showed that many individuals, including Veterans, were using complementary and integrative health (CIH) approaches. In 1998, the NIH formed the National Center for Complementary and Alternative Medicine (NCCAM). Since its inception it has funded research for and supported the use of acupuncture in certain pain conditions^4^ In 2011, the Office of Patient Centered Care and Cultural Transformation (OPCC&CT) was established by the Veteran’s Health Administration, and in 2014 leadership launched the Integrative Health Coordinating Center (IHCC) to work to bring CIH approaches to the VA. In 2017, the VHA Whole Health System of care included acupuncture as one of the complementary and integrative health modalities, VHA Directive 1137-Provision of Complementary and Integrative Health, included in the VA’s medical benefits package.^5^

The VA strives to promote evidence-based practice and utilizes evidence maps such as this to provide guidance to VA leadership and to inform policy and clinical decision-making. The original Evidence Synthesis Program (ESP) report published in 2014 by VA Health Services Research & Development (HSR&D) has for years been among the most highly downloaded report from the ESP database.^6^ With the increasing popularity of acupuncture among both Veterans and civilians and a growing body of available research on acupuncture, an update of this report was essential.