# APPENDIX F PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 3 | Yes | Thank you.
3 | 4 | Yes | Thank you.
4 | 5 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
5 | 1 | No | Thank you.
6 | 3 | No | Thank you.
7 | 4 | No | Thank you.
8 | 5 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked?
9 | 1 | Yes - These two meta-analyses by the Acupuncture Trialists Collaboration (over 20,000 individual patients) have been very influential in many of the guidelines that have been established for acupuncture and pain--but I do not see them included. I understand that especially the updated version may not have met your criteria for inclusion because it did not include a systematic review per se. But I wonder if there is some way to add a mention of this work to the discussion given its importance in the evolution of the field. One of the important things about this work is that they had enough individual patients to analyze separately the studies that compared to sham and those that compared to usual care--demonstrating much larger difference in effects when no sham comparison was included. Since sham acupuncture has an effect generally larger than most placebo controls, the use of this methodology in the past may have contributed to an underestimate of the true effect of real acupuncture, which is what is relevant to clinicians and patients. You mention in the conclusion that more studies are needed comparing to conditions other than sham--but you do not really address the impact that sham as the dominant comparison in the past may have had on the ultimate conclusions of the systematic reviewers.; Vickers AJ, Cronin AM, Maschino AC, . Acupuncture for Chronic Pain: Individual Patient Data Meta-analysis. Arch Intern Med. 2012;172(19):1444–1453. doi:10.1001/archinternmed.2012.3654 22965186; Vickers AJ, Vertosick EA, Lewith G, .; Acupuncture Trialists’ Collaboration. Acupuncture for chronic pain: update of an individual patient data meta-analysis. J Pain. 2018;19(5):455–474 29198932 .; If you’d like I could write you few lines on this to include in the Discussion--and could cite the Vickers work there perhaps :) | This is a really excellent point. The original Vickers review was included in the prior version of this evidence map. But the updated Vickers review was not included in this map because the updated Vickers review did not assess certainty of evidence, which was a criterion for inclusion. But, since the Vickers review was an individual patient data meta-analysis, which is an inherently stronger type of review than a conventional review, we were essentially penalizing it for being good. Fortunately, in the Vickers review they also presented the results of their data as a conventional meta-analysis, and thus we were able to apply the GRADE criteria to come up with a certainty of evidence rating for their conclusion – and thus we are able to get it onto the map.
10 | 3 | No
11 | 4 | No
12 | 5 | No
Additional suggestions or comments can be provided below.
13 | 1 | See above | Thank you for your comment!
14 | 3 | Page 6- paragraph “Purpose” Would be appreciated if there was an added sentence designating that this publication is not intended to reflect established policy recommendations for clinical practice more explicitly. | Thank you for your comment. This is addressed in existing text on page 2: “The findings and conclusions in this document are those of the author(s) who are responsible for its contents and do not necessarily represent the views of the Department of Veterans Affairs or the United States government. Therefore, no statement in this article should be construed as an official position of the Department of Veterans Affairs.”
15 | 3 | Page 6- line 20-21 “Acupuncture is a technique that is part of a larger system of care originating in China and other Asian countries dating back to the 12th century.” the sentence is not very clear. The historicity of the origins of traditional Chinese medicine definitely take it back farther than the 12th century, the origin of acupuncture on the other hand as originating exclusively during the Song Dynasty is also very contested. | We worked with the reviewer to revise this part of the introduction.
16 | 3 | Page 8 paragraph “Data Sources and Searches” - Although this is later clarified in appendix a, line 5-6 appear to state that only studies from 2012 and early 2013 were included. Appendix A clarifies by stating that studies were included through 2021. | This has been corrected.
17 | 3 | Including multiple comparators in the study instead of insisting on only “sham vs acupuncture” was very appreciated in order to capture a more robust date set. | This has been corrected
18 | 3 | Page 9 paragraph “Synthesis” - perhaps an explanation as to why a different convention was chosen for the bubble plot in this publication versus the previous publication evidence map from 2014 would be helpful to understand the intentions of the authors. Why do the plots look so different? To the untrained reader who might try to compare the studies there would be difficulty with reconciling this? An explanation of the rationale for this choice would be appreciated. | We have added a sentence to explain why this is, basically to provide more and better information than was available for the older report.
19 | 3 | Page 14 - line 20 and onward - the choice of “high certainty” is difficult to see as different than “high rate of effectiveness”. This choice seems to impact the appearance of the bubble plots and the few “high certainty” studies seem to appear as if there are few conditions for which there is “high rate of effectiveness”. This is clear to the academic, but difficult to glean for the casual reader in my opinion. | An important feature of GRADE is that the certainty of evidence is separated from the size of the effect of the intervention. Thus, bodies of evidence can report estimates of large effect but low certainty and conversely, evidence of low effect but high certainty. We have added this to the report. A review concluding “high rate of effectiveness” but with Low certainty of evidence should be considered as a conclusion for which the authors felt the true effect might be substantially different than that reported.
20 | 3 | Page 27 - paragraph “Future Research” was very thoughtful and inclusive and will likely result in much fruitful direction for researchers in this field, this paragraph is an excellent contribution to the academic community. | Thank you for your comment!
21 | 4 | None
22 | 5 | Page 3: line 27. Requestor is from VA Central Iowa, but this request really came through Juli Olson’s role in the Integrative Health Coordinating Center under the Office of Patient Centered Care & Cultural Transformation. | This has been corrected.
23 | 5 | Page 6, line 11: Could this be updated to reflect the request came from the IHCC? | This has been corrected.
24 | 5 | Page 10, line 6: A little confusing here because auricular acupuncture is manual. It might be better to classify between auricular and comprehensive or full-body acupuncture. Electro-acupuncture can also be done to the ear. So maybe: “For type of acupuncture, triangle denotes studies that used exclusively auricular acupuncture and circle denotes all other types of comprehensive or full body acupuncture (manual/standard, electro-acupuncture).” This also may have included auricular acupuncture in some of the studies, but I don’t know if that is the case. | We have made the change to clarify the definition for the type of acupuncture in text.
25 | 5 | Page 16, Figure 2: Suggest changing the title of bubble “Hormone therapy - Related SE in Br Ca” to “Related SE in Br Ca associated with hormone therapy” because the table reads “Benefit for acupuncture…Hormone therapy” acupuncture is not effective for hormone therapy, it is effective for the SE. Then it would read “Benefit for acupuncture…Related SE in Br Ca…” | This has been corrected.
26 | 5 | Page 16, Figure 2: “dental surgical pain” is post-operative? There is a tradition of doing dental surgery with acupuncture over other anesthesia so reader might think of that. Perhaps “Post-Op Dental Pain” | This has been corrected.
27 | 5 | Page 22, line 30: Consider hyphenating Posttreatment (post-treatment). | This has been corrected.
28 | 5 | Page 27, line 51: This is a very helpful statement, thank you: “Studies comparing acupuncture to placebo or sham are probably not the priority, rather the priority should be studies comparing acupuncture to other recommended/accepted/active therapies for the condition.” | Thank you for your comment!
29 | 5 | Page 28: This is a helpful comment about the state of the literature: “This seems to be a mismatch between resources and need. The field of acupuncture would be best moved forward with resources devoted to producing more high quality RCTs and producing fewer new systematic reviews.” | Thank you for your comment!
30 | 5 | Question about depression and the Smith review. Table 4 on page 22 lists the results from the study about risks rather than symptomatic improvement for depression: “It is unclear whether there are differences in the risk of adverse events between persons receiving acupuncture or sham acupuncture” But the study concludes: “We found low-quality evidence suggesting that acupuncture (manual and electro-) may moderately reduce the severity of depression by end of treatment (SMD −0.66, 95% CI −1.06 to −0.25, five trials, 488 participants).” Depression ended up in the evidence map as no benefit or harm from acupuncture. I am confused here. | Because the effectiveness conclusions from that review were rated as Low certainty of evidence and the adverse events conclusion was Moderate certainty of evidence, the Low certainty conclusion never made it to the evidence map because the columns are mutually exclusive. We have solved this problem by splitting out all conclusions about adverse events into their own map, thus leaving the main maps to be only about effectiveness outcomes, and now that review does enter as one where all conclusions were rated as Low or Very Low.
31 | 5 | In the evidence maps did anything end up in the “No benefit or harm” category due to harm? I appreciated the review assessing risk and harm for acupuncture, but maybe it would be helpful to spell out that there is no study that was put in that category to do the findings of harm. Could that category even be updated to “no benefit” since none showed harm? | We have now split out the adverse events/harms into their own map, and the main maps are now just “benefit” vs. “no benefit”.