# APPENDIX E CONCLUSIONS FROM SYSTEMATIC REVIEWS INCLUDED IN THE EVIDENCE MAP

Angina

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Yang, 2019^64^ | None | Compared with sham acupuncture, acupuncture may be associated with improving average pain intensity, 6-Min Walk Test, anxiety symptoms, and depression symptoms. | Very Low to Moderate | 17

Ankle Pain

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Kim, 2014^39^ | None | We are unable to conclude whether acupuncture is more effective than other standard methods for the treatment of ankle sprains in adults because of the very low quality of the available evidence. Because the adverse effects of acupuncture treatment were not described in most of the studies, we are also unable to draw any conclusions about the safety of acupuncture. | Very Low | 19

Anxiety

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Tong, 2021^44^ | Pre-Operative Anxiety | Acupuncture therapy, compared with sham therapy, significantly reduced the STAI-S score for patients with preoperative anxiety. | Very Low to Moderate | 5

Back Pain

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Chou, 2017^10^ | Chronic Low Back Pain (Radicular Back Pain) | Acupuncture vs sham acupuncture: moderate magnitude of effect for pain; no effect for function; Acupuncture vs no acupuncture: moderate magnitude of effect for pain; moderate for function | Low | 9
Chou, 2017^10^ | Acute Low Back Pain | Acupuncture vs sham small magnitude of effect for pain; no effect for function | Low | 9
Skelly, 2020^20^ | Chronic Low Back Pain | Acupuncture was associated with a small improvement in short-term function compared with sham acupuncture or usual care; there was no difference between acupuncture and controls in intermediate-term or long-term function. | Low | 8
Skelly, 2020^20^ | Chronic Low Back Pain | Acupuncture was associated with small improvements in short-term and long-term pain compared with sham acupuncture, usual care, an attention control, or a placebo intervention, but there was no difference in intermediate-term pain. | Low | 8
Tang, 2018^40^ | Low Back Pain - Herniated Disc | Acupuncture was better than traction and diclofenac sodium at improvements in VAS pain. | Very Low | 30

Cancer-related Pain

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Hu, 2016^24^ | Pain Management in Cancer | Acupuncture plus drug therapy is more effective than conventional drug therapy alone, but acupuncture alone is not more effective than conventional drug therapy.; Acupuncture is not more effective than sham acupuncture. | Very Low | 20
Hwang, 2020^23^ | Chemotherapy-induced Peripheral Neuropathy | Acupuncture was more effective than pharmacological treatment. | Low | 5
Lin, 2019^65^ | Health-related Quality of Life in Cancer Patients | Acupuncture has no effect on health-related quality of life. | Low | 4
Yuanqing, 2020^22^ | Hormone Therapy-Related Side Effects in Breast Cancer Patients | Acupuncture is a moderately appropriate alternative therapy for hormone therapy-related side effects in breast cancer patients. | Low | 20

Carpal Tunnel Syndrome

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Choi, 2018^17^ | None | No clear difference in acupuncture vs sham- short term follow-up: 8 weeks / 3 months | Very Low to Low | 10
Choi, 2018^17^ | None | No clear difference in clinical improvement between acupuncture vs oral corticosteroid-short term follow-up: 4 weeks / 13 months | Very Low | 10
Choi, 2018^17^ | None | Better clinical improvement with acupuncture vs corticosteroids in long-term follow-up: 7 months / 13 months | Very Low | 10
Choi, 2018^17^ | None | No clear difference in rates of improvement in acupuncture vs vitamin B12 - short term follow-up | Very Low | 10
Choi, 2018^17^ | None | No clear difference in rates of improvement in electro-acupuncture vs night splints - short term follow-up | Very Low | 10
Choi, 2018^17^ | None | There was more clinical improvement in acupuncture vs ibuprofen-short term follow-up: 4 weeks | Very Low | 10

Chronic Fatigue Syndrome

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Wang, 2014^11^ | None | There were significant better effects in acupuncture group compared with sham as measured by the Chalder’s Fatigue Scale (physical) score. | Low to Moderate | 7
Zhang, 2019^66^ | None | In summary, acupuncture appears more effective than sham acupuncture and Chinese herbal medicine for the treatment of CFS. | Very Low to Low | 13

Chronic Musculoskeletal Pain

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Vickers, 2018^16^ | None | Acupuncture is effective for the treatment of chronic pain compared with sham and control, with treatment effects persisting over time. | Moderate | 39

Depression

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Liu, 2021^45^ | Post-stroke Depression | Acupuncture combined with conventional treatment could significantly reduce post-stroke depression. Acupuncture was safer than anti-depressants. | Very Low to Low | 17
Smith, 2018^47^ | None | The reduction in severity of depression was less when acupuncture was compared with control acupuncture than when acupuncture was compared with no treatment control.; The reduction in severity of depression with acupuncture given alone or in conjunction with medication versus medication alone is uncertain.; The effect of acupuncture compared with psychological therapy is unclear. Acupuncture did however have a positive effect on physical quality of life at the end of treatment when compared with sham acupuncture. | Very Low to Low | 64
Smith, 2019^46^ | Depression in Pregnancy | Acupuncture compared to control may reduce antenatal depression. | Moderate | 2
Sorbero, 2016^48^ | Major Depressive Disorder | Acupuncture may be superior to waitlist; limited evidence suggests a higher rate of responders with adjunctive acupuncture plus anti-depressants compared with anti-depressants alone. | Low | 18

Dysmenorrhea

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Smith, 2016^56^ | None | There is insufficient evidence to demonstrate whether acupuncture is effective in treating primary dysmenorrhea, and for most comparisons no data were available on adverse events. | Very Low to Low | 32

Fertility

Author, Year | Sub condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Coyle, 2021^57^ | Assistive Reproductive Therapy | When compared with sham acupuncture, acupuncture performed at the time of embryo transfer does not result in better outcomes for live birth rate or for miscarriage rate. | High | 6
Jo, 2017^60^ | Polycystic Ovary Syndrome / Ovarian Hyperstimulation | Acupuncture may increase the clinical pregnancy rate and ongoing pregnancy rate and decrease the risk of Ovarian Hyperstimulation Syndrome in women with Polycystic Ovarian Syndrome undergoing in vitro fertilization or intracytoplasmic sperm injection. | Low | 4
Kwan, 2018^59^ | Oocyte Retrieval | Compared to conscious sedation alone, more effective pain relief during oocyte retrieval was reported when conscious sedation was combined with electro-acupuncture. No significant increase in pregnancy rate. | Low | 7
Lim, 2019^58^ | Anovulatory Infertility | There was no evidence of any clinically relevant differences in live birth rate, multiple pregnancy rate, ovulation rate, clinical pregnancy rate, and miscarriage rate in sham vs acupuncture. | Low | 8
Lim, 2019^58^ | Anovulatory Infertility | We were uncertain whether acupuncture improved ovulation rate compared to active treatment. | Very Low | 8

Fibromyalgia

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Kim, 2019^26^ | Pain, Fatigue, Sleep Quality | Verum acupuncture is more effective than sham acupuncture for pain relief, improving sleep quality, and improving general status in fibromyalgia syndrome posttreatment. | Moderate to High | 10
Zhang, 2019^27^ | None | Compared with sham, real acupuncture was more effective in reducing pain and improving quality of life after treatment in the short term. | Low to Moderate | 12
Zhang, 2019^27^ | None | At follow-up in the long term, the effect of acupuncture was also superior to that of sham acupuncture. | Low | 12

Functional Dyspepsia

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Pang, 2016^67^ | None | Acupuncture therapy has a similar effect for functional dyspepsia in comparison with sham acupuncture. | Low | 16
Pang, 2016^67^ | None | Acupuncture therapy is superior to medication (prokinetic agents) in improving the symptoms and quality of life of functional dyspepsia patients. | Low | 16

Headache

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Giovanardi, 2020^28^ | Migraine | Acupuncture is mildly more effective and much safer than medication for the prophylaxis of migraine. | Moderate | 9
Linde, 2016^32^ | Tension-type Headache | Acupuncture reduces headache frequency over usual care and sham. | Moderate | 12
Linde, 2016^31^ | Migraine | Compared with no acupuncture, acupuncture was associated with a moderate reduction of headache frequency over no acupuncture after treatment. | Moderate | 22
Linde, 2016^31^ | Migraine | Comparison with sham, both after treatment and at follow-up, acupuncture was associated with a small but statistically significant frequency reduction over sham. | Moderate | 22
Linde, 2016^31^ | Migraine | Compared with prophylactic drug treatment, acupuncture reduced migraine frequency significantly more than drug prophylaxis after treatment. | Moderate | 22
Xu, 2018^30^ | Migraine Headache without Aura | Acupuncture had a significant advantage over medication in reducing frequency of migraine, pain score, and effective rate.; Acupuncture also had a significant advantage over sham acupuncture in reducing frequency of migraine and pain score. | Very Low to Low | 14
Yun, 2020^29^ | Occipital Neuralgia | Acupuncture was more effective that medication at reducing VAS pain. | Very Low | 11
Yun, 2020^29^ | Occipital Neuralgia | Acupuncture was more effective than medication on the total effective rate. | Low | 11

Herpes Zoster

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Cui, 2021^68^ | None | When compared with antiviral therapy, acupuncture was associated with a significant reduction in pain, a significant reduction in incrustation time, and a significant reduction in decrustation time. | Low | 21
Cui, 2021^68^ | None | Compared with active treatment, acupuncture was associated with reduction on the overall incidence of post-herpetic neuralgia | Moderate | 21

Inflammatory Bowel Disease

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Wang, 2020^69^ | None | Acupuncture may be more effective in treating ulcerative colitis compared to conventional medicine (metronidazole combined with sulfasalazine). | Low to Moderate | 13

Insomnia

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Cao, 2019^50^ | Primary Insomnia | Acupuncture might result in improvement compared to no treatment on Pittsburgh Sleep Quality Index scores and appears safe. | Very Low to Low | 73
Kwon, 2020^49^ | Insomnia in Elderly | Using Pittsburgh Sleep Quality Index score, acupuncture and acupuncture combined with relaxation were both more effective in improving sleep quality compared to relaxation alone. | Very Low to Moderate | 13

Irritable Bowel Syndrome

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Guo, 2020^70^ | None | Compared with loperamide, acupuncture showed more effectiveness in weekly defecation. Compared to dicetel, acupuncture produced more significant effect related to the total symptom score and IBS Symptom Severity Scale. | Low to Moderate | 31

Lateral Elbow Pain

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Navarro-Santana, 2020^14^ | None | Evidence suggests positive effects of acupuncture, but not electro-acupuncture, for pain, related disability, and strength, in lateral epicondylalgia of musculoskeletal origin, in the short term. | Very Low to Low | 14

Menopause

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Dodin, 2013^61^ | None | When acupuncture was compared with sham acupuncture, there was no evidence of any difference in their effect on hot flushes. When acupuncture was compared with no treatment, there appeared to be a benefit from acupuncture, but acupuncture appeared to be less effective than HT. | Very Low to Low | 16

Mixed Not Specified Pain

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Chia, 2018^13^ | Painful Conditions in Emergency Department | Acupuncture was superior with sham acupuncture, more effective than intravenous morphine, comparable to conventional Emergency Department treatment, and superior to standard Emergency Department care alone when used on an adjuvant basis. | Low | 6
Liu, 2019^12^ | Post-stroke Shoulder-Hand Syndrome | Acupuncture therapy seems effective for motor function, pain relief, and activities of daily living in stroke patients with mild Shoulder-hand Syndrome, when it is used in combination with rehabilitation. | Low | 38
Xiang, 2017^41^ | Immediate Pain Relief in Musculoskeletal Pain Conditions | Acupuncture was associated with a greater immediate pain relief effect compared with sham acupuncture. | Moderate | 13
Xiang, 2017^41^ | Immediate Pain Relief in Musculoskeletal Pain Conditions | Acupuncture was associated with greater immediate pain relief effect when compared to analgesic injections. | Low | 13

Neck Pain

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Skelly, 2020^20^ | Chronic Neck Pain | Acupuncture was associated with small improvements in short-term and intermediate-term function versus sham acupuncture, a placebo (sham laser), or usual care. | Low | 11
Skelly, 2020^20^ | Chronic Neck Pain | There were no differences in pain in trials comparing acupuncture with sham acupuncture or placebo interventions in the short term. | Low | 11
Skelly, 2020^20^ | Chronic Neck Pain | There was insufficient evidence to draw conclusions regarding short-term function or pain for acupuncture versus NSAIDs. | Low | 11
Skelly, 2020^20^ | Chronic Neck Pain | No serious adverse events were reported in 6 trials reporting harms. | Low | 11

Osteoarthritis

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Manheimer, 2018^42^ | Hip Pain | Acupuncture probably has little or no effect in reducing pain or improving function relative to sham acupuncture in people with hip osteoarthritis. | Moderate | 6
Skelly, 2020^20^ | Knee Pain | There were no differences between acupuncture versus control interventions (sham acupuncture, waitlist, or usual care) on function in the intermediate term | Low | 9
Skelly, 2020^20^ | Knee Pain | There were no clinically meaningful differences between acupuncture versus control interventions (sham acupuncture, waitlist, or usual care) on pain in the intermediate term. | Moderate | 9

Other Acute Pain

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Chou, 2020^19^ | Post-operative Pain | There is inconsistent evidence on acupuncture’s effect on pain intensity when compared with sham. Acupuncture may be associated with decrease analgesic use after 1 day compared to usual care. | Very Low | 2
Chou, 2020^19^ | Dental Surgical Pain | There is insufficient evidence of acupuncture’s effect on post-operative pain compared with sham acupuncture. | Very Low | 1
Chou, 2020^19^ | Kidney Stone | Acupuncture was not effective in reducing pain intensity vs medication for kidney stone. | Low | 1

Other Chronic Pain - Various

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Eccleston, 2017^18^ | Chronic Non-cancer Pain | There is no evidence for the efficacy or safety of electro-acupuncture for reducing prescribed opioid use in chronic pain. | Very Low | 1

Other Specific

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Zhou, 2020^71^ | Improvement of Cognitive Impairment After Stroke | Acupuncture was effective in improving PSCI (post-stroke cognitive impairment) compared to no treatment or sham. | Moderate | 37

Pelvic Pain

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Franco, 2019^9^ | Chronic Prostatitis/Chronic Pelvic Pain Syndrome | Acupuncture probably reduced prostatitis symptoms (compared with sham). | Moderate | 6
Franco, 2019^9^ | Chronic Prostatitis/Chronic Pelvic Pain Syndrome | Acupuncture may have reduced prostatitis symptoms compared with medical treatment | Moderate | 6

Peripheral Neuropathy

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Ju, 2017^33^ | None | There is insufficient evidence to support or refute the use of acupuncture for neuropathic pain in general or for any specific neuropathic pain condition when compared with sham acupuncture or other active therapies. | Very Low to Low | 6

Peripheral Neuropathy (Diabetic)

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Amato, 2019^25^ | None | Evidence for acupuncture was insufficient for diabetic peripheral neuropathy. | Very Low | 1

Post-herpetic Neuralgia

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Pei, 2019^34^ | None | Acupuncture was more effective in reducing post-herpetic neuralgia pain intensity compared to control. | Low to Moderate | 4

Post-operative Pain

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Tedesco, 2017^37^ | None | Acupuncture reduced or delayed opioid consumption compared with sham or no treatment. | Low to Moderate | 4
Yin, 2020^36^ | None | Compared to active treatment, acupuncture may improve the overall symptoms of Postcholecystectomy syndrome (PCS). | Low to Moderate | 14
Zimpel, 2020^35^ | Post-caesarean Pain | We are very uncertain if acupuncture (versus no treatment) or acupuncture plus analgesia (versus placebo plus analgesia) has any effect on pain because the quality of evidence is very low. Acupuncture plus analgesia (versus analgesia) may reduce pain at 12 hours and 24 hours. | Very Low | 4

Posttraumatic Stress Disorder

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Grant, 2018^51^ | None | Needle acupuncture reduces PTSD and depressive symptoms at follow-up compared to passive controls, treatment-as-usual, and active interventions. No significant differences were observed between acupuncture and comparators for other outcomes. | Very Low to Low | 7

Pregnancy

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Liddle, 2015^63^ | Low Back and Pelvic Pain | There was evidence from single studies that acupuncture significantly improves evening pelvic pain better than stabilizing exercise or usual prenatal care. | Moderate | 4
Liddle, 2015^63^ | Low Back and Pelvic Pain | There is evidence suggesting that acupuncture is better than physiotherapy at relieving evening low back and pelvic pain and related functional disability, and improves pain, but not women’s ability to carry out daily activities, when started at 26- rather than 20-weeks’ gestation. | Low | 4

Premenstrual Syndrome

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Armour, 2018^62^ | None | Acupuncture may reduce overall mood and physical PMS symptoms when compared with sham. There was not enough evidence to determine the safety of acupuncture. | Low | 4

Primary Ovarian Insufficiency

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Jo, 2015^55^ | Resumption of Menses | Acupuncture was better than comparison treatments in the resumption of menses. | Low | 6
Jo, 2015^55^ | Resumption of Menses | There are insufficient data to reach conclusions about the effect of acupuncture on symptoms. | Very Low | 6

Primary Trigeminal Neuralgia

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Hu, 2019^38^ | None | Acupuncture might have some positive effects for primary trigeminal neuralgia. | Very Low to Low | 33

Schizophrenia

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Shen, 2014^52^ | None | Limited evidence suggests that acupuncture may have some antipsychotic effects as measured on global and mental state with few adverse effects. | Very Low to Low | 30

Shoulder Pain

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Yuan, 2016^21^ | None | Acupuncture is superior to sham acupuncture in relief of pain. | High | 5
Ben-Arie, 2020^43^ | Frozen Shoulder | Acupuncture could be safe and effective for pain reduction, restoring shoulder function, and restoring flexion ROM for frozen shoulder patients in the short term and midterm. | Very Low | 13

Substance Use Disorder

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Chen, 2018^53^ | Opioid Use Disorder | Acupuncture may be effective for alleviating some symptoms compared with sham and no treatment. | Very Low to Low | 9
Chen, 2018^53^ | Opioid Use Disorder | There was insufficient evidence to suggest better effect of acupuncture compared with medication. | Moderate | 9
White, 2014^54^ | Tobacco Use Disorder | Compared with sham, acupuncture resulted in greater short-term smoking cessation. | Moderate | 19

Temporomandibular Joint Dysfunction

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Yuan, 2016^21^ | None | Real acupuncture showed a favorable effect on pain relief compared with sham. | Moderate | 13

Tinnitus

Author, Year | Sub-condition | Conclusion | Certainty of Evidence | Total Number of Studies Included for Acupuncture
Savage, 2014^15^ | None | Unclear if acupuncture is effective in people with tinnitus. | Low | 1