# APPENDIX D CONDITIONS AND SUB-CONDITIONS OF INCLUDED SYSTEMATIC REVIEWS

Condition | Sub-Condition | Map
Angina^64^ | None | Other
Ankle Sprain/Pain^39^ | None | Musculoskeletal Pain
Anxiety | Pre-operative Anxiety^44^ | Mental Health
Back Pain | Chronic Low Back Pain^20^ | Musculoskeletal Pain
Back Pain | Low Back Pain - Herniated Disc^40^ | Musculoskeletal Pain
Back Pain | Chronic Low Back Pain (Radicular Back Pain)^10^ | Musculoskeletal Pain
Back Pain | Acute Low Back Pain^10^ | Musculoskeletal Pain
Cancer-related Pain | Hormone Therapy-related Side Effects in Breast Cancer Patients^22^ | Musculoskeletal Pain
Cancer-related Pain | Chemotherapy-induced Peripheral Neuropathy^23^ | Pain
Cancer-related Pain | Health-related Quality of Life in Cancer Patients^65^ | Other
Cancer-related Pain | Pain Management in Cancer^24^ | Pain
Carpal Tunnel Syndrome^17^ | None | Pain
Chronic Fatigue Syndrome^66^ | None | Other
Chronic Fatigue Syndrome^11^ | None | Other
Chronic Musculoskeletal Pain^16^ | None | Musculoskeletal Pain
Depression | Post-stroke Depression^45^ | Mental Health
Depression | Depression in Pregnancy^46^ | Mental Health
Depression^47^ | None | Mental Health
Depression | Major Depressive Disorder^48^ | Mental Health
Diabetic Peripheral Neuropathy^25^ | None | Pain
Dysmenorrhea^56^ | None | Women’s Health
Dyspepsia | Functional Dyspepsia^67^ | Other
Fertility | Assistive Reproductive Therapy^57^ | Women’s Health
Fertility | Anovulatory Infertility^58^ | Women’s Health
Fertility | Oocyte Retrieval^59^ | Women’s Health
Fertility | Polycystic Ovary Syndrome / Ovarian Hyperstimulation^60^ | Women’s Health
Fibromyalgia | Pain, Fatigue, Sleep Quality^26^ | Pain
Fibromyalgia | None | Pain
Headache | Migraine, Active Therapy^28^ | Pain
Headache | Occipital Neuralgia^29^ | Pain
Headache | Migraine Headache Without Aura^30^ | Pain
Headache | Migraine, Mixed Comparators^31^ | Pain
Headache | Tension-type Headache^32^ | Pain
Herpes Zoster^68^ | None | Other
Inflammatory Bowel Disease^69^ | None | Other
Irritable Bowel Syndrome^70^ | None | Other
Insomnia | Insomnia in Elderly^49^ | Mental Health
Insomnia | Primary Insomnia^50^ | Mental Health
Lateral Elbow Pain^14^ | None | Musculoskeletal Pain
Menopause^61^ | None | Women’s Health
Mixed Pain - Not Specified | Painful Conditions in Emergency Department^13^ | Other
Mixed Pain - Not Specified | Immediate Pain Relief in Musculoskeletal Pain Conditions^41^ | Musculoskeletal Pain
Mixed Pain - Not Specified | Post-stroke Shoulder-hand Syndrome^12^ | Musculoskeletal Pain
Neck Pain | Chronic Neck Pain^20^ | Musculoskeletal Pain
Osteoarthritis | Knee Pain^20^ | Musculoskeletal Pain
Osteoarthritis | Hip Pain^42^ | Musculoskeletal Pain
Other Acute Pain | Post-operative Pain^19^ | Pain
Other Acute Pain | Dental Pain^19^ | Pain
Other Acute Pain | Kidney Stone^19^ | Pain
Other Chronic Pain - Various | Chronic Non-cancer Pain^18^ | Pain
Other Specific Pain | Acupuncture for Improving Cognitive Impairment After Stroke^71^ | Other
Peripheral Neuropathy^33^ | None | Pain
Premenstrual Syndrome^62^ | None | Women’s Health
Post-herpetic Neuralgia^34^ | None | Pain
Post-operative Pain | Post-caesarean Pain^35^ | Women’s Health
Post-operative Pain | Post-operative Pain, Active Therapy^36^ | Pain
Post-operative Pain | Post-operative Pain, Mixed Comparators^37^ | Pain
Pregnancy | Low Back and Pelvic Pain^63^ | Women’s Health
Primary Ovarian Insufficiency | Resumption of Menses^55^ | Women’s Health
Primary Trigeminal Neuralgia^38^ | None | Pain
Prostatitis - Chronic Pelvic Pain | Chronic Prostatitis/Chronic Pelvic Pain Syndrome^9^ | Pain
Posttraumatic Stress Syndrome^51^ | None | Mental Health
Schizophrenia^52^ | None | Mental Health
Shoulder Pain | Frozen Shoulder^43^ | Musculoskeletal Pain
Shoulder Pain | None^21^ | Musculoskeletal Pain
Substance Use Disorder | Opioid Use Disorder^53^ | Mental Health
Substance Use Disorder | Tobacco Use Disorder^54^ | Mental Health
Temporomandibular Pain^21^ | None | Musculoskeletal Pain
Tinnitus^15^ | None | Other