# APPENDIX C EXCLUDED PUBLICATIONS

## Not Reviewed in Detail in Favor of a Better SR on Same Topic, N = 33

1 Amaral, L.K.B., ., Efficacy of conservative therapy in older people with nonspecific low back pain: A systematic review with meta-analysis and GRADE recommendations. Arch Gerontol Geriatr, 2020. 90: p. 104177.32682168
2 Asher, G.N., ., Comparative Benefits and Harms of Complementary and Alternative Medicine Therapies for Initial Treatment of Major Depressive Disorder: Systematic Review and Meta-Analysis. J Altern Complement Med, 2017. 23(12): p. 907–919.28700248
3 Bisson, J.I., ., Non-pharmacological and non-psychological approaches to the treatment of PTSD: results of a systematic review and meta-analyses. Eur J Psychotraumatol, 2020. 11(1): p. 1795361.33029330
4 Cheong, Y.C., ., Acupuncture and assisted reproductive technology. Cochrane Database Syst Rev, 2013(7): p. Cd006920.23888428
5 Close, C., ., A systematic review investigating the effectiveness of Complementary and Alternative Medicine (CAM) for the management of low back and/or pelvic pain (LBPP) in pregnancy. J Adv Nurs, 2014. 70(8): p. 1702–16.24605910
6 Dai, L., ., Acupuncture and Derived Therapies for Pain in Palliative Cancer Management: Systematic Review and Meta-Analysis Based on Single-Arm and Controlled Trials. J Palliat Med, 2021.
7 Deare, J.C., ., Acupuncture for treating fibromyalgia. Cochrane Database Syst Rev, 2013. 2013(5): p. Cd007070.23728665
8 Gao, R., ., Acupuncture and clomiphene citrate for anovulatory infertility: a systematic review and meta-analysis. Acupunct Med, 2020. 38(1): p. 25–36.31581787
9 Gutke, A., ., Treatments for pregnancy-related lumbopelvic pain: a systematic review of physiotherapy modalities. Acta Obstet Gynecol Scand, 2015. 94(11): p. 1156–67.26018758
10 He, Y., ., Clinical Evidence for Association of Acupuncture and Acupressure With Improved Cancer Pain: A Systematic Review and Meta-Analysis. JAMA Oncol, 2020. 6(2): p. 271–278.31855257
11 Hou, S., ., Treatment of Chemotherapy-Induced Peripheral Neuropathy: Systematic Review and Recommendations. Pain Physician, 2018. 21(6): p. 571–592.30508986
12 Huang, J.F., ., Can Acupuncture Improve Chronic Spinal Pain? A Systematic Review and Meta-Analysis. Global Spine J, 2020: p. 2192568220962440.
13 Jo, J., Y.J. Lee, and H. Lee, Acupuncture for polycystic ovarian syndrome: A systematic review and meta-analysis. Medicine (Baltimore), 2017. 96(23): p. e7066.28591042
14 Kizhakkeveettil, A., K. Rose, and G.E. Kadar, Integrative therapies for low back pain that include complementary and alternative medicine care: a systematic review. Glob Adv Health Med, 2014. 3(5): p. 49–64.25568825
15 Kolber, M.R., ., PEER systematic review of randomized controlled trials: Management of chronic low back pain in primary care. Can Fam Physician, 2021. 67(1): p. e20–e30.33483410
16 Lan, L., ., Acupuncture for functional dyspepsia. Cochrane Database Syst Rev, 2014(10): p. Cd008487.25306866
17 Li, C., ., The response-time relationship and covariate effects of acupuncture for chronic pain: A systematic review and model-based longitudinal meta-analysis. Eur J Pain, 2020. 24(9): p. 1653–1665.32533885
18 Metcalf, O., ., Efficacy of Fifteen Emerging Interventions for the Treatment of Posttraumatic Stress Disorder: A Systematic Review. J Trauma Stress, 2016. 29(1): p. 88–92.26749196
19 Mu, J., ., Acupuncture for chronic nonspecific low back pain. Cochrane Database Syst Rev, 2020. 12: p. Cd013814.33306198
20 Mulla, S.M., ., Management of Central Poststroke Pain: Systematic Review of Randomized Controlled Trials. Stroke, 2015. 46(10): p. 2853–60.26359361
21 Nascimento, P., ., Effectiveness of interventions for non-specific low back pain in older adults. A systematic review and meta-analysis. Physiotherapy, 2019. 105(2): p. 147–162.30563712
22 Seo, S.Y., ., Effectiveness of Acupuncture and Electroacupuncture for Chronic Neck Pain: A Systematic Review and Meta-Analysis. Am J Chin Med, 2017. 45(8): p. 1573–1595.29121797
23 Smith, C.A., ., Acupuncture or acupressure for pain management during labour. Cochrane Database Syst Rev, 2020. 2(2): p. Cd009232.32032444
24 Tang, H., ., Acupuncture for Lateral Epicondylitis: A Systematic Review. Evid Based Complement Alternat Med, 2015. 2015: p. 861849.26843886
25 Trinh, K., ., Acupuncture for neck disorders. Cochrane Database Syst Rev, 2016(5): p. Cd004870.
26 Wahbeh, H., ., Complementary and Alternative Medicine for Posttraumatic Stress Disorder Symptoms: A Systematic Review. J Evid Based Complementary Altern Med, 2014. 19(3): p. 161–175.24676593
27 Wu, J., D. Chen, and N. Liu, Effectiveness of acupuncture in polycystic ovary syndrome: A systematic review and meta-analysis of randomized controlled trials. Medicine (Baltimore), 2020. 99(22): p. e20441.32481448
28 Xiang, Y., ., Evidence of efficacy of acupuncture in the management of low back pain: a systematic review and meta-analysis of randomised placebo- or sham-controlled trials. Acupunct Med, 2020. 38(1): p. 15–24.31526013
29 Xie, Z.Y., ., The effects of acupuncture on pregnancy outcomes of in vitro fertilization: a systematic review and meta-analysis. BMC Complement Altern Med, 2019. 19(1): p. 131.31200701
30 Yu, C., ., Effectiveness of acupuncture for angina pectoris: a systematic review of randomized controlled trials. BMC Complement Altern Med, 2015. 15: p. 90.25888363
31 Yuan, Q.L., ., Traditional Chinese medicine for neck pain and low back pain: a systematic review and meta-analysis. PLoS One, 2015. 10(2): p. e0117146.25710765
32 Zhong, Y., ., Acupuncture in improving endometrial receptivity: a systematic review and meta-analysis. BMC Complement Altern Med, 2019. 19(1): p. 61.30866920
33 Zhou, Y., ., Effectiveness of Acupuncture for Lateral Epicondylitis: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Pain Res Manag, 2020. 2020: p. 8506591.32318130

## Duplicate, N = 3

1 Franco, J.V., ., Non-pharmacological interventions for treating chronic prostatitis/chronic pelvic pain syndrome. Cochrane Database Syst Rev, 2018. 5(5): p. Cd012551.29757454
2 Pennick, V. and S.D. Liddle, Interventions for preventing and treating pelvic and back pain in pregnancy. Cochrane Database Syst Rev, 2013(8): p. Cd001139.23904227
3 Zimpel, S.A., ., Complementary and alternative therapies for post-caesarean pain. Cochrane Database of Systematic Reviews, 2020(9).

## Review of Reviews, N = 2

1 Huang, J., ., Acupuncture for the Treatment of Alzheimer’s Disease: An Overview of Systematic Reviews. Front Aging Neurosci, 2020. 12: p. 574023.33328956
2 Wang, L.Y., ., Overview of Meta-Analyses of Five Non-pharmacological Interventions for Alzheimer’s Disease. Front Aging Neurosci, 2020. 12: p. 594432.33324194

## No Outcome of Interest, N = 1

1 Wong, V., ., Acupuncture for acute management and rehabilitation of traumatic brain injury. Cochrane Database Syst Rev, 2013(3): p. Cd007700.23543554

## Not an Intervention of Interest, N = 1

1 Lan, Y., ., Auricular acupuncture with seed or pellet attachments for primary insomnia: a systematic review and meta-analysis. BMC Complement Altern Med, 2015. 15: p. 103.25886561

## Comparison, N = 1

1 Mo, Z., ., Comparisons of the Effectiveness and Safety of Tuina, Acupuncture, Traction, and Chinese Herbs for Lumbar Disc Herniation: A Systematic Review and Network Meta-Analysis. Evid Based Complement Alternat Med, 2019. 2019: p. 6821310.31015852