# APPENDIX A SEARCH STRATEGIES

## PubMed

1 March 2013-present; English

Search Run: 22 April 2021

Acupuncture

AND

systematic[sb]

AND

(“2013/03/01”[PDat] : “3000/12/31”[PDat])

Results: 1165

## CDSR

2013-present; English

Search Run: 22 April 2021

acupuncture:ti,ab,kw

Results: 85

## DARE (via CRD)

Publication Year 2013 – 2021 (However – ends at 2014 when DARE ceased production)

Any Field: acupuncture

AND

Title: systematic review

Results: 74 – 5 identified non-English = 69

## AMED (via Dialog)

1 March 2013 – 22 April 2021; English

ti(acupuncture) AND (“systematic review”)

OR

ab(acupuncture) AND (“systematic review”)

Results: 148