# Evidence Brief: Doula Support for Veterans

## PREFACE

The VA Evidence Synthesis Program (ESP) was established in 2007 to provide timely and accurate syntheses of targeted health care topics of importance to clinicians, managers, and policymakers as they work to improve the health and health care of Veterans. These reports help:

- Develop clinical policies informed by evidence;
- Implement effective services to improve patient outcomes and to support VA clinical practice guidelines and performance measures; and
- Set the direction for future research to address gaps in clinical knowledge.

The program comprises four ESP Centers across the US and a Coordinating Center located in Portland, Oregon. Center Directors are VA clinicians and recognized leaders in the field of evidence synthesis with close ties to the AHRQ Evidence-based Practice Center Program. The Coordinating Center was created to manage program operations, ensure methodological consistency and quality of products, interface with stakeholders, and address urgent evidence needs. To ensure responsiveness to the needs of decision-makers, the program is governed by a Steering Committee composed of health system leadership and researchers. The program solicits nominations for review topics several times a year via the program website (https://www.hsrd.research.va.gov/publications/esp/TopicNomination.cfm).

The present report was developed in response to a request from the VHA Office of Women’s Health, Reproductive Health Division. The scope was further developed with input from Operational Partners (below) and the ESP Coordinating Center review team.

## ACKNOWLEDGMENTS

The authors are grateful to Kathryn Vela, MLIS for literature searching; Sarah Young, MPH for data abstraction efforts and editorial and citation management support; Melissa Olsen, DONA and Fatima Abdallah, CD for their subject matter expertise; and the following individuals for their contributions to this project:

### Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Amanda M. Johnson, MD, FACOG
  Director, Reproductive Health Division
  VHA Office of Women’s Health

### Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix D in Supplemental Materials for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.

## EXECUTIVE SUMMARY

#### Background

The Evidence Synthesis Program Coordinating Center is responding to a request from the VHA Office of Women’s Health, Reproductive Health Division, for an Evidence Brief on the benefits of doula support for pregnant, birthing, and postpartum Veterans. Findings from this brief will be used to inform development and piloting of a VA doula support program, which is intended to support the best possible maternal and infant outcomes for Veterans.

#### Methods

To identify studies, we searched MEDLINE, Cochrane Database of Systematic Reviews, Cochrane Central Register of Controlled Trials, and other sources up to January 4, 2022. We used prespecified criteria for study selection, data abstraction, and rating internal validity and strength of the evidence. See the Methods section and our PROSPERO protocol for full details of our methodology.

Key Findings

- Doula support may be associated with reduced rate of cesarean births, reduced use of oxytocin or Pitocin, reduced use of epidural, shorter duration of labor, and higher Apgar scores for neonates.
- Doula support could be associated with reduced labor pain, fewer low birthweight neonates, and fewer NICU admissions, but more well-designed studies with clear adherence to doula intervention are needed to better determine impact.
- No evidence of harms of doula support or support by layperson companionship during labor were identified.
- Evidence on doula support is generally limited by inconsistency in study methodologies and intervention definitions, and future research to identify key program components and optimal intervention characteristics is warranted.

Women are the fastest-growing US Veteran cohort, largely due to the dramatic increase in women entering and separating from military service over the last half century. With the increased number of Veteran women, the Veterans Health Administration (VHA) has experienced greater demand for tailored health services for Veteran women. VHA currently provides maternity care through purchased care in the community, and also employs Maternity Care Coordinators to navigate care for pregnant Veterans with their providers in and outside the VHA to ensure access to needed resources during pregnancy and the postpartum period. Pregnant Veterans may be at increased risk for adverse pregnancy outcomes due to complex medical and mental health conditions, underscoring the need for comprehensive well-coordinated maternity care.

Contemporary maternal labor and delivery care often consists of a hospital-based birth with a team of obstetrical medical providers, and ideally added support from a birth companion of the pregnant person’s choice. One model of providing support to the pregnant person is through the use of trained labor support from a doula. Doulas act as both coaches and companions to the pregnant individual and provide a range of reproductive care services depending on their degree of training and the clinical care setting. The most comprehensive care provided by doulas (hereafter referred to as full-spectrum care) includes prenatal visits with childbirth education for expectant families, support during labor and delivery, postpartum care, lactation support, miscarriage support, and support for the loss of a pregnancy or stillbirth if needed. In the US, doula credentialing is not a requirement and is not standardized, but several organizations have developed training programs that range from weekend workshops to a full range of coursework and examination. In non-US settings, the role of a doula may be performed by a layperson (such as a close relative) with minimal training.

Supportive care during labor may enhance physiological labor processes and maternal feelings of agency and confidence in their own ability to successfully navigate the labor. In this way, it has been proposed that doula care may lead to reduced use of epidurals or other interventions (eg, oxytocin or Pitocin). The aim of the present report was to synthesize available evidence on the benefits and harms of doula support programs, with a focus on maternal, infant, and delivery outcomes as well as implementation characteristics of successful doula support initiatives. The report is intended to inform VHA policymaking related to comprehensive maternity care provided for pregnant Veterans.

We identified 41 relevant studies whose findings are summarized in Table ES-1 and Table ES-2. Included studies most often addressed delivery outcomes, followed by maternal and infant outcomes. Included studies suggest that trained doulas could be associated with a reduced rate of cesarean birth, whereas layperson doulas may reduce or have no effect on cesarean rates. We also found evidence that doula care by either trained or lay doulas could reduce or have no association with labor augmentation with oxytocin and reduction in labor pain. Both trained and layperson doula support was associated with shortened duration of labor, whereas only trained doula support appeared to have an association with reduction in epidural use. Importantly, this review did not identify any harms related to intrapartum doula care. With respect to neonatal outcomes, included studies suggest possible benefits of doula support on Apgar scores, frequency of low birth weight neonates, and neonatal intensive care unit (NICU) admission, and doula support did not appear to have negative impact.

Table ES-1 Summary of Findings – Trained Doula Support

Outcome | Strength of Evidence (SOE) | Summary
Maternal and Delivery Outcomes
Maternal Mortality; w/ Trained Doula Support | 1 Cohort/non-RCT; Insufficient SOE | Trained doula support may not be associated with maternal mortality
Cesarean; w/ Trained Doula Support | 12 RCTs; 13 Cohort/non-RCTs; Moderate SOE | Trained doula support may be associated with reduced rate of cesarean
Oxytocin/Pitocin use; w/ Trained Doula Support | 10 RCTs; 2 Cohort/non-RCTs; Moderate SOE | Trained doula support is likely associated with reduced or no difference in the use of oxytocin or Pitocin
Epidural use; w/ Trained Doula Support | 11 RCTs; 6 Cohort/non-RCTs; Moderate SOE | Trained doula support is likely associated with reduced or no difference in the use of epidural.
Labor Pain; w/ Trained Doula Support | 2 RCTs; 3 Cohort/non-RCTs; Low SOE | Trained doula support may be associated with reduced or no difference in labor pain
Duration of Labor; w/ Trained Doula Support | 12 RCTs; 3 Cohort/non-RCTs; Moderate SOE | Trained doula support is likely associated with shorter duration of labor
Neonatal Outcomes
Infant Mortality; w/ Trained Doula Support | 1 Cohort/non-RCTs; Insufficient SOE | It is unclear whether trained doula support impacts infant mortality
Apgar Score; w/ Trained Doula Support | 9 RCTs; 7 Cohort/non-RCTs; Low SOE | Trained doula support may or may not be associated with better Apgar scores
Low Birth Weight; w/ Trained Doula Support | 2 RCTS; 4 Cohort/non-RCTs; Low SOE | Trained doula support may be associated with reduced or no difference in rates of low birth weight
NICU Admission; w/ Trained Doula Support | 3 RCTs; 1 Cohort/non-RCT; Low SOE | Trained doula support may be associated with lower or no difference in NICU admissions

Abbreviations. NICU=neonatal intensive care unit; RCT=randomized controlled trial; SOE=strength of evidence.

Available evidence on doula support has several important limitations. We were limited in our ability to compare findings across studies due to inconsistencies in study design and methodology, as well as the inconsistent and diverse definitions of trained labor support, its duration, and the varying quality and scope of doula training. Some studies also did not provide a clear description of how doula programs may have been implemented or relied on retrospective medical record review for presence of support person with no other descriptors on support provided. Common limitations among the RCTs included lack of information on non-adherence to interventions and lack of information on missing data. Limitations of observational studies included lack of information on doula support implementation and adherence, self-selection of patients into doula and control groups, and lack of statistical analysis.

In summary, available evidence suggests that full-spectrum trained doula support services in the form of continuous support during labor and delivery may be beneficial to birthing individuals. Specifically, we found that this type of support may improve birth (eg, higher 5-minute Apgar scores and reduced NICU admission) and maternal delivery outcomes (eg, reduced need for cesarean, reduced need for Pitocin/oxytocin). We found no evidence of harms of doula support or support by layperson companionship during labor. Evidence on doula support is generally limited by inconsistency in study methodologies and intervention definitions. Future research to identify key program components and optimal intervention characteristics is warranted.

Table ES-2 Summary of Findings – Layperson as Doula Support

Outcome | Strength of Evidence (SOE) | Summary
Maternal and Delivery Outcomes
Cesarean; w/ Layperson as Doula Support | 5 RCTs; 3 Cohort/non-RCTs; Low SOE | Layperson as doula support may not be associated with reduced rate of cesarean
Oxytocin/Pitocin Use; w/ Layperson as Doula Support | 5 RCTs; Moderate SOE | Layperson as doula support is likely associated with reduced or no difference in the use of oxytocin or Pitocin
Epidural Use; w/ Layperson as Doula Support | 1 RCT; Insufficient SOE | Layperson as doula support is not likely associated with the use of epidural
Labor Pain; w/ Layperson as Doula Support | 3 RCTs; Low SOE | Layperson as doula support may be associated with reduced or no difference in labor pain
Duration of Labor; w/ Layperson as Doula Support | 5 RCTs; 1 Cohort/non-RCTs; Moderate SOE | Layperson as doula support is likely associated with shorter duration of labor
Neonatal Outcomes
Apgar Score; w/ Layperson as Doula Support | 3 RCTs; 2 Cohort/non-RCTs; Low SOE | Layperson as doula support may be associated with better or no difference in Apgar scores
NICU Admission; w/ Layperson as Doula Support | 1 RCT; 1 Cohort/non-RCT; Low SOE | Layperson as doula support may be associated with lower NICU admissions

Abbreviations. NICU=neonatal intensive care unit; RCT=randomized controlled trial; SOE=strength of evidence.

## INTRODUCTION

### PURPOSE

The ESP Coordinating Center (ESP CC) is responding to a request from the Veterans Health Administration (VHA) Office of Women’s Health, Reproductive Health Division, for an Evidence Brief on the benefits of doula support for pregnant, birthing, and postpartum Veterans. Findings from this Brief will be used to inform development and piloting of a US Department of Veterans Affairs (VA) doula support program, which is intended to support the best possible maternal and infant outcomes for Veterans.

### BACKGROUND

Over the last half century, the number of women entering and retiring from military services has increased dramatically^1^ and has resulted in Veteran women being the fastest-growing US Veteran cohort.^2^ In 1973, women composed only 2% of the enlisted forces and 8% of the officer corps. Today, they represent 16% of enlisted personnel and 19% of officers,^3^ and by some estimates, female service members will make up more than 16% of the total US Veteran population by 2042.^4^ With the increased number of Veteran women, the Veterans Health Administration (VHA) has experienced greater demand for tailored health services for Veteran women and their female partners/dependents of Veterans. VHA currently provides maternity care through purchased care in the community, and also employs Maternity Care Coordinators (MCCs) to navigate care for pregnant Veterans with their providers in and outside the VHA to ensure access to needed resources during pregnancy and the postpartum period.^5^

Coordination of comprehensive maternity care with ongoing VHA care is necessary, in part, due to the complex medical and mental health conditions that may increase pregnant Veterans’ risk for adverse pregnancy outcomes.^6^ Veteran women have been shown to have a higher risk of gestational diabetes and hypertensive disorders of pregnancy^7^ and may experience higher rates of spontaneous abortion and ectopic pregnancies than their non-Veteran counterparts.^8^ High rates of military sexual trauma have also been found to be associated with poor birth outcomes including lower infant birth weight, less likelihood of full-term birth, and higher risk of postpartum depression.^9^ Additionally, Veteran women may be entering pregnancy with musculoskeletal conditions that could influence the trajectory of their pregnancy and birth. Musculoskeletal conditions are among the most common diagnoses in women returning from deployment and women are more likely to have back pain, joint disorders, and other musculoskeletal disorders after military service than their male counterparts.^10^

Contemporary maternal labor and delivery (L&D) care often consists of a hospital-based birth with a team of obstetrical medical providers. Birth companions or doulas can provide complementary continuous labor support throughout a pregnancy and are a globally recommended model of care. Doulas act as both coaches and companions to the pregnant individual and provide a range of reproductive care services depending on their degree of training and the clinical care setting. The most comprehensive care provided by doulas includes prenatal visits with childbirth education for expectant families, support during labor and delivery, postpartum care, lactation support, miscarriage support, and support for the loss of a pregnancy or stillbirth if needed.^11^ In the US, doula credentialing is not a requirement and is not standardized, but several organizations have developed training programs that range from weekend workshops to a full range of coursework and examination. In non-US settings, the role of a doula may be performed by a layperson (such as a close relative) with minimal training.

The American College of Obstetricians and Gynecologists (ACOG) cites doula support as “one of the most effective tools to improve labor and delivery,”^12^ as trained and experienced doulas can fill important gaps in maternal health care by providing continuous physical and emotional support during pregnancy, childbirth, and the postpartum period.^13^ High rates of cesarean birth and the use of medical interventions during labor in the US are associated with significant morbidity and mortality.^14^ One of the leading causes of primary cesarean delivery is arrested labor, which in the hospital setting is often addressed with the use of oxytocin.^15^ Supportive care during labor may enhance physiological labor processes and maternal feelings of agency and confidence in the birthing person’s ability to successfully navigate the labor, possibly reducing the need for labor interventions such as use of oxytocin or epidural analgesia.^15^

The aim of the present report was to synthesize available evidence on the benefits and harms of doula support programs, with a focus on maternal, infant, and delivery outcomes as well as implementation characteristics of successful doula support initiatives. The report is intended to inform VHA policymaking related to comprehensive maternity care provided for pregnant Veterans.

## METHODS

### PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42022302806).

### KEY QUESTIONS

The following key questions (KQs) were the focus of this review:

KQ1 What are the benefits and harms of doula support programs to maternal and neonatal outcomes?
KQ2 What are the implementation characteristics of doula support programs shown to improve maternal and infant outcomes?

### ANALYTIC FRAMEWORK

The analytic framework shown in Figure 1 provides a conceptual overview of this review. The benefits and harms of doula support programs in terms of maternal outcomes (maternal mortality/morbidity, labor pain, and complications resulting from labor), neonatal outcomes (infant mortality, Apgar scores, low birth weight, neonatal intensive care unit stay), and delivery outcomes (cesarean, duration of labor need for labor augmentation) were of interest (KQ1). Implementation characteristics of doula support programs shown to improve maternal and infant outcomes were also of interest (KQ2).

Figure 1 Analytic Framework

Abbreviations. CLS=continuous labor support; KQ=key question; NICU=neonatal intensive care unit.

### ELIGIBILITY CRITERIA

The ESP included studies that met the following criteria:

Population | Pregnant, birthing, or postpartum adults
Intervention | Doula support (ie, one-on-one emotional support during pregnancy, labor, and/or postpartum)
Comparator | No doula support (ie, pregnant, birthing, or postpartum adults not receiving doula support)
Outcomes | - KQ1: Maternal mortality and severe morbidity (as defined by (https://www.cdc.gov/reproductivehealth/maternalinfanthealth/smm/severe-morbidity-ICD.htm) the Centers for Disease Control and Prevention; excluding blood product transfusion), neonatal outcomes (eg, low birth weight, neonatal intensive care unit stay), and reduction in low-risk cesarean delivery (ie, nulliparous, term, singleton, vertex [NTSV^a^] cesarean births); - KQ2: Implementation characteristics (eg, level of training, timing [ie, during pregnancy, birthing, or postpartum period])
Timing | Any
Setting | Any
Study Design | Any, but we may prioritize articles using a best-evidence approach to accommodate Evidence Brief timeline.

Note.

a Nulliparous, Term, Singleton, Vertex (NTSV) describes a live birth at or beyond 37.0 weeks gestation, in the individual’s first pregnancy, that are singleton (no twins or beyond) and in the vertex presentation (no breech or transverse positions), via cesarean birth.

### DATA SOURCES AND SEARCHES

To identify articles relevant to the key questions, a research librarian searched Ovid MEDLINE, CINHAL, Cochrane Database of Systematic Reviews, and ClinicalTrials.gov, as well as AHRQ and HSR&D databases, through January 2022 using terms for doula support and labor/birth companions (see Appendix A in Supplemental Materials for complete search strategies). Additional citations were identified from hand-searching reference lists of existing systematic reviews and consultation with content experts. We included all relevant studies from 2 systematic reviews^15,16^ and 1 meta-analysis^16^ of relevant studies encompassing this topic. We limited the search to published and indexed articles involving human subjects available in the English language. Study selection was based on the eligibility criteria described above. Studies of labor support by trained professionals such as registered nurses (RNs), nurse practitioners (NPs), midwives, or other labor and delivery professionals were excluded. Titles, abstracts, and full-text articles were reviewed by 1 investigator and checked by another using an online systematic review platform (PICO Portal^17^). All disagreements were resolved by consensus or discussion with a third investigator.

### DATA ABSTRACTION AND ASSESSMENT

Effect information and population, intervention, and comparator characteristics were abstracted from all included studies. The internal validity (risk of bias) of each included study was rated using the ROBINS-I tool for observational studies^18^ and the Cochrane risk of bisk tool for randomized controlled trials (RCTs).^19^ All data abstraction and internal validity ratings were first completed by 1 investigator and then checked by another; disagreements were resolved by consensus or discussion with a third investigator.

We graded the strength of the evidence (SOE) for each outcome based on the AHRQ Methods Guide for Comparative Effectiveness Reviews.^20^ This approach provides a rating of confidence in reported findings based on trial methodology (design, quality, and risk of bias), consistency (whether effects are in the same direction and have a consistent magnitude), and directness (whether assessed outcomes are clinically important to patients and providers). When information on precision of findings (eg, confidence intervals) is available, certainty of evidence is also evaluated. For this review, we applied the following general algorithm: high strength evidence consisted of multiple, large studies with low risk of bias, consistent and precise findings, and clinically relevant outcomes; moderate strength evidence consisted of multiple studies with low to unclear risk of bias, consistent and precise findings, and clinically relevant outcomes; low strength evidence consisted of a single study, or multiple small studies, with unclear to high risk of bias, inconsistent or imprecise findings, and/or outcomes with limited clinical relevance; and insufficient evidence consisted of a single study with unclear or high risk of bias, or no available studies.

### SYNTHESIS

We synthesized the evidence narratively by outcomes (maternal and delivery, and neonatal), and by type of doula/continuous labor support (trained doula support and layperson doula support).

## RESULTS

### LITERATURE FLOW

The literature flow diagram (Figure 2) summarizes the results of the study selection process (full list of excluded studies available in Appendix B in Supplemental Materials).

Figure 2 Literature Flowchart

Abbreviations. CDSR=Cochrane Register of Systematic Reviews; CINAHL=Cumulative Index of Nursing and Allied Health; NHS=National Health Service (UK).

### LITERATURE OVERVIEW

Our search identified 381 potentially relevant articles after deduplication and initial title and abstract screening. We included 41 primary studies (in 42 publications), which are summarized in Table 1 (see Appendix C in Supplemental Materials for full study details).

Most studies^21–52^ examined the impact of trained doula support (eg, certified doulas, traditional birth attendants [TBAs], or doula-trained labor and delivery staff such as nurses, midwives, or Lamaze coaches). The remaining studies^53–61^ examined the effect of untrained labor support (eg, family members, partners, or friends) who provided companionship to the birthing individual and had less than 2 hours of instruction or were provided no birthing education. Among the 41 studies reporting patient sample size, the median sample size was 8,979 (range: 34 to 280,087), with 5 studies including more than 10,000 patients in their sample by utilizing national data or retrospective medical record data. We identified 13 studies in progress (see Appendix F in Supplemental Materials) examining perinatal birth outcomes or maternal satisfaction outcomes related to continuous labor support utilizing trained doulas.

Of the studies that met inclusion criteria, 22 were RCTs, 7 were prospective cohort studies, 11 were retrospective cohort studies, and 1 was a non-randomized controlled trial. Most studies were rated as unclear risk of bias, and only 6 of 41 included studies were rated as low risk of bias. Common limitations among the RCTs included lack of information on non-adherence to interventions and lack of information on missing data. Limitations of observational studies included lack of information on doula support implementation and adherence, self-selection of patients into doula and control groups, and lack of statistical analysis.

Table 1 Characteristics of Included Studies

Study; Country; Design | N | Population | Intervention Characteristics | Comparator | Outcomes Assessed
Trained Doula Support (Certified Doula, TBA, or Trained L&D Staff)
Austad 2020^21^; Guatemala; Cohort | 782 | Birthing persons under TBA care as part of coverage of the MHA program. | TBAs trained as OCNs within the rural Maya villages in Guatemala | No OCN Services | Cesarean birth; Duration of labor; Infant mortality
Bolbol-Haghighi 2016^22^; Iran; RCT | 100 | Pregnant adult with expected normal childbirth, without presence of disease, depression, or pregnancy complications | Midwifery students trained for supportive care by a skilled midwife | Routine care | Cesarean birth; Oxytocin/Pitocin use; Apgar score
Byrskog 2020^23^; Sweden; Cohort | 17,699 | Migrant birthing persons in Sweden who had received CBD services between 2008 and 2016 | CBDs bilingual in Swedish and the birthing person’s own language trained by registered midwives with CBD accreditation | Routine care | Cesarean birth; Epidural use; Apgar score; Low birth weight
Campbell 2006^24^; US; RCT | 600 | Nulliparous, singleton, low-risk pregnant persons able to identify female friend or family to act as doula | Female friend or relative who had 2 sessions (2hrs) of labor support training | Control group had support people of their own choosing, but not doula-trained | Cesarean birth; Epidural use; Duration of labor; Apgar score
Chen 2020^25^; Northern Taiwan; Cohort | 220 | Pregnant individuals able to communicate in Chinese or Taiwanese with term pregnancies ≥38 weeks | DONA-certified doulas | Routine care | Cesarean birth; Oxytocin/Pitocin use; Apgar score
Cogan 1988^26^; US; RCT | 34 | Pregnant persons (primigravids and multigravidas) at 26 to 37 weeks’ gestation | Lamaze childbirth preparation instructor acting as a doula throughout labor | Routine care | Epidural Use; Oxytocin/Pitocin use; Duration of labor; Apgar score; Low birth weight; NICU admission
Dickinson 2002^27^; Australia; RCT | 992 | Nulliparous pregnant persons with uncomplicated singleton fetus at term, cervical dilatation <5 cm, | Midwifery Support + pharmacologic and nonpharmacologic alternatives to epidural | Epidural for pain relief only | Cesarean birth; Epidural use; Duration of labor; Apgar score
Dundek 2006^28^; US (Somali community); Cohort | 348 | Somali birthing persons who have been served by a Somali doula have given birth to live infants at this hospital | Hospital-based on-call DONA certified Somali women providing culturally competent doula care to Somali patients | Non-doula attended Somali births | Cesarean birth
Feng 2013^29^; China; Cohort | 400 | The primiparas with singleton fetus with uncomplicated singleton fetus at term | Doula Midwife + EPI; Doula Midwife + analgesia | No support and no EPI | Cesarean birth; Oxytocin/Pitocin use; Labor pain; Duration of labor
Fulton 2011^30^; US; Cohort | 60 | Primiparas, currently receiving public health insurance, English/Spanish speaking, not scheduled for C-section, ≤5 cm dilated | Doula midwife (identified through medical record review, no details provided). | Routine care | Epidural use; Labor pain; Apgar score
Gagnon 1997^31^; Gagnon 1999^62^; Canada; RCT | 413 | Singleton pregnancies >37 weeks gestation, in labor and stimulated with oxytocin | Nurse 1:1 support during labor and birth | Routine care | Cesarean birth; Oxytocin/Pitocin use; Epidural use; Duration of labor; Apgar score; NICU admission
Goedkoop 2009^32^; UK; Cohort | 140 | Active NHS doulas in 2008 | Doula support during birth and postnatal - any setting | NHS statistics for general maternity services | Cesarean birth; Epidural use
Gordon 1999^33^; US; RCT | 314 | Nulliparous uncomplicated pregnancies in labor w/ cervix <5 cm dilated, >18 years old | Hospital based doula with CBD training | Routine care | Cesarean birth; Oxytocin/Pitocin use; Epidural use
Gruber 2013^34^; US; Cohort | 226 | Expectant individuals who attended at least 3 childbirth classes through Healthy Moms Healthy Babies program | Certified doula support during prenatal, birth, and postpartum period + childbirth education; Doula support and at least 2 pre and 2 post-partum visits | Routine care | Maternal complications Cesarean birth
Hans 2018^35^; US; RCT | 312 | Birthing persons meeting sociodemographic risk criteria from HFA/PAT models | Doula and home-visit services including pre/post-natal visits. | Pregnancies referred to available case management services | Cesarean birth; Epidural use; Low birth weight; NICU admission
Hodnett 2002^36^; US & Canada; RCT | 6915 | Singleton or twin pregnancies >34 weeks gestation and established labor at time of randomization giving birth at a hospital with cesarean rates >15%, excluded if they were already expecting support with a doula | Continuous labor support by trained labor support nurse | Routine care | Cesarean birth; Epidural use; Apgar score
Isbir 2017^37^; Turkey; RCT | 72 | >18 years old, literate, primary education, ≥37 weeks gestation, ≤3 cm dilation, participants were excluded if they underwent cesarean birth, primipara or multipara, no contraindications to normal/vaginal birth | Midwifery students with obstetrics training in their 3rd year | Routine care | Labor pain; Duration of labor
Kashanian 2010^38^; Iran; RCT | 100 | Nulliparous birthing persons aged 18-34 (low risk), with gestational age 38-42 weeks, live singleton fetus, cephalic presentation and expected normal birth weight | Midwife providing 1:1 support during labor, patient education from midwife | Routine care | Cesarean birth; Oxytocin/Pitocin use; Duration of labor; Apgar score
Kennell 1991^39^; US; RCT | 616 | Nulliparous birthing persons, aged 13-34, with singleton uncomplicated pregnancy. | Trained doula who underwent 3-week training | Routine care | Cesarean birth; Oxytocin/Pitocin use; Epidural use; Duration of labor
Kozhimannil 2013^40^; US; Cohort | 280,087 | Medicaid-funded singleton births and/or Medicaid beneficiaries | Everyday Miracles doula (DONA certified) | Routine care | Cesarean birth; Epidural use; Low Birth weight
Kozhimannil 2014^41^; US; Cohort | 2400 | Birthing persons who gave birth to single infant in US hospital between 7/1/2011 and 6/30/2012, aged 18-45 | Doula/trained labor assistant | Individuals with no doula support and individuals who indicated desire for doula care but did not have it | Cesarean birth
Langer 1998^42^; Mexico; RCT | 724 | Single fetus, no previous vaginal delivery, <6 cm dilated, no indications of severe obstetric disease or elective C-section | Doula accompanied mother without interruption throughout labor, childbirth, and immediate post-partum period. | Routine care | Cesarean birth; Epidural use; Duration of labor; Apgar score
Lesser 2005^43^; US; RCT | 221 | Patients >35 weeks of gestation, single gestation, English-speaking, no indication of elective C-section | Volunteer layperson, trained by La Leche League members | Routine care | Cesarean birth; Oxytocin/Pitocin use; Epidural use; Duration of labor
McGrath 2008^44^; US; RCT | 420 | Nulliparous birthing persons 18-41 years in the 3rd trimester of an uncomplicated pregnancy, expected to be accompanied during labor by their male partner | Trained doula support | Routine care | Cesarean birth; Oxytocin/Pitocin use; Epidural use; Apgar score
Mottl-Santiago 2008^45^; US; Cohort | 11,471 | Birthing persons giving birth at Boston Medical Center | Birth Sisters program providing support throughout active labor, birth, and the first several hours postpartum | No Birth Sisters program support | Cesarean birth; Epidural use; Apgar score
Nommsen-Rivers 2009^46^; US; Cohort | 169 | Primiparous, low-income birthing persons without known high-risk condition, English/Spanish speaking, within 20-mile radius of hospital, not scheduled for C-section, ≤5 cm cervical dilation | Trained volunteers who provided support through L&D, and 2 home post-partum visits | Routine care | Labor pain Apgar score
Ravangard 2017^47^; Iran; RCT | 150 | Nulliparous birthing persons, 16 to 44 years of age, gestational age of at least 32 weeks, no pregnancy complications, cephalic presentation | Doula presence during delivery (details of support NR) | Other non-medical methods of support (hot shower, aromatherapy, etc) | Labor pain
Shelp 2004^63^ US (Somali community) Cohort | 104 | Somali birthing persons | Trained Somali layperson | No Somali doula support | Cesarean birth Apgar score
Spiby 2015^49^; UK; Cohort | 507 | Disadvantaged birthing persons, referred to doula services | Trained volunteer doulas | Routine care | Cesarean birth Low birth weight NICU admission
Thomas 2017^50^; US; Cohort | 489 | Birthing persons who met WIC requirements in Black & Latino neighborhoods of Brooklyn, NY | Certified, full spectrum doulas subcontracted to support Healthy Start Brooklyn. | Non HSB program participants | Cesarean birth Low birth weight
Trueba 2000^51^; Mexico; RCT | 100 | Birthing persons at term, engaged in an active phase of labor, exhibited ≥3 cm cervical dilatation, were nulliparous, had no previous uterine incision, and possessed adequate pelvises | Students from the Lamaze International Childbirth Educator program at Anahuac University under supervision of trained doula | Routine care | Cesarean birth; Oxytocin/Pitocin use; Duration of labor
Zhang 2018^52^; China; Cohort | 579 | Birthing persons | Current or retired nurses with experience in midwifery and healthcare in the hospital | TENS unit; OR; Epidural analgesia | Apgar score; Duration of labor
Layperson as Doula (Partner, Friend or Relative)
Gadappa 2021^53^; India; Cohort | 8,749 | Birthing persons with singleton live fetus with cephalic presentation ≥37 weeks of gestational age, low risk, planning to deliver in hospital | Female friend/relative | Usual delivery care | Maternal complications; Cesarean birth; Apgar score; NICU admission
Hofmeyr 1991^54^; South Africa; RCT | 189 | Nulliparous birthing persons in active labor, without obstetric complications, <6 cm dilated | Lay volunteer trained in CLS by the researchers | Usual delivery care | Labor pain; Cesarean birth; Apgar score
Kabakian-Khasholian 2018^55^; Egypt, Lebanon, Syria; Cohort | 2,491 | Low-risk birthing persons (aged >18) who arrived at the hospital with a female relative and who were planning a vaginal birth | Female relative provided with IEC materials | Usual delivery care | Cesarean birth; Apgar score
KC 2020^56^; Nepal; Cohort | 10,321 | Birthing persons at 22+ weeks of gestation | Labor companion | Usual delivery care | Infant mortality; Cesarean birth; Low birth weight
Klaus 1986^57^; Guatemala; RCT | 417 | Primigravids in early labor with cervical dilation of ≤3 cm | Guatemalan layperson with no obstetric training provided constant support and companionship | Usual delivery care | Cesarean birth NICU admission
Madi 1999^58^; Botswana; RCT | 109 | Primigravids with singleton pregnancy, no history of complications, 38-42 weeks gestation, and cephalic presentation | Female relative support | Usual delivery care | Cesarean birth Apgar score
Morhason-Bello 2009^59^; Nigeria; RCT | 585 | Pregnant singleton birthing persons with anticipated vaginal delivery, without previous caesarean, intrauterine fetal death, planned induction, multiple pregnancy, malpresentation, and/or chronic medical disorders | Labor companion | Usual delivery care | Labor pain; Cesarean birth
Safarzadeh 2012^60^; Iran; RCT | 150 | Primiparous birthing persons in active labor with singleton pregnancy without severe obstetric disease | Female relative | Usual delivery care | Labor pain
Yuenyong 2012^61^; Thailand; RCT | 120 | Birthing | Female relative | Usual delivery care | Cesarean birth Apgar score

Abbreviations. CBD=community-based doula; CLS=continuous labor support; DONA=Doulas of North America; EPI=epidural analgesia; HFA=Health Families America; HSB=Health Start Brooklyn; IEC=information, communication, & education; L&D=labor & delivery; MHA=Mayan Health Alliance; NHS=National Health Services; NICU=newborn intensive care unit; NR=not reported; OCN=obstetric care navigators; PAT=Parents as Teachers; RCT=randomized controlled trial; TBA=traditional birth attendant; TENS=transcutaneous electrical nerve stimulation; UK=United Kingdom; US=United States.

Notes. Apgar Score (appearance, pulse, grimace, activity, respiration) refers to a newborn assessment comprised of five components (color, heart rate, reflexes, muscle tone, and respiration), each scored as 0, 1, or 2, and the normative total value is >7 out of 10.

### EFFECTIVENESS OF DOULA SUPPORT

#### Maternal and Delivery Outcomes

##### Maternal Mortality

It is unclear whether doula support impacts maternal mortality; our confidence in these findings is limited as this outcome was reported by a single observational study reporting maternal mortality outcomes (insufficient SOE) with wide variation in how the intervention was implemented across different locations.^21^ This study reported no maternal deaths among indigenous communities in Guatemala who were provided trained TBAs as obstetric care navigators (OCNs) to connect birthing individuals to clinics as needed for medical intervention (ie, providing medical intervention for high-risk patients) or among those without OCN support.

##### Cesarean Delivery

Trained doula support is likely associated with reduced rate or no difference in cesarean delivery rates, our confidence in these findings is moderate (moderate SOE) as they are supported by a large number of studies (N = 25) consistently reporting a reduction in or generally low rates of cesarean delivery with some methodological concerns. Of the 25 studies identified thatused trained doula support, 7 studies^25,29,38,39,44,51,63^ reported lower rates of cesarean compared with no doula support, and 10 studies^27,28,31,32,34,36,42–45,50^ reported low rates of cesarean, but no significant differences between groups. Seven studies^23,24,33,35,40,41,49^ reported similar rates of cesarean across groups. A single study^21^ reported slightly higher rates of cesarean among doula-supported births, but in this study (described above), an increase in cesarean suggests that the doulas had escalated emergent cases to clinical care, as was the intent of the intervention.

Laypersons as doula support may also be associated with a reduced rate of cesarean delivery, but our confidence in these findings is low (low SOE) due to a smaller number of studies (N = 8) with inconsistent findings across studies and some study methodological limitations. Among the 8 studieswhere a layperson provided doula support, 4 studies^53,57–59^ reported lower cesarean rates with doula support, and 2 reported generally lower cesarean rates (nonsignificant).^54,61^ The remaining 2 studies^55,56^ reported higher rates of cesarean in supported groups. However, the studies reporting higher cesarean rates were likely limited by recall bias (semi-structured interviews conducted without consideration for time elapsed since the birth occurred) and inconsistent data collection methods in 1 study,^56^ and variation in intervention birthing policies, intervention adherence, and time that the doula was allowed to spend with the birthing person among study locations in the second study.^55^

##### Oxytocin/Pitocin Use

Consistent findings from 12 generally well-conducted studies indicated that trained doula support is likely associated with reduced or no difference in the use of oxytocin or Pitocin to accelerate labor progress (moderate SOE). Of the 12 studies reporting oxytocin or Pitocin use in births supported by a trained doula, 4 studies^38,39,44,51^ reported significantly lower use of oxytocin or Pitocin use in doula-supported births. A single prospective cohort study from Taiwan,^25^ rated as high risk of bias based on high numbers of unexplained excluded participants and poor detail on participant selection, reported higher use of oxytocin or Pitocin in doula-supported births (66/97 [67.4%] vs 12/55 [33.3%], p < .001), while the remaining 7 studies (in 8 publications)^22,26,29,31,33,37,43,62^ reported similar rates of usage across groups with no significant differences in oxytocin or Pitocin use.

Layperson as doula support is also likely associated with reduced use of oxytocin or Pitocin to accelerate labor progress. Five studies consistently reported reduced rates of oxytocin or Pitocin use with layperson doula support (moderate SOE). All 5 studies^57–61^ reported lower use of oxytocin or Pitocin use in births supported by layperson as doula support. While 2 well-conducted studies^57,58^ reported a statistically significant lower use of oxytocin or Pitocin, the 3 remaining studies^59–61^ reported lower rates of use with non-significant differences in oxytocin or Pitocin use.

##### Epidural Use

Findings from 17 studies consistently reported that trained doula support is likely associated with a reduced rate or no difference in the rates of epidural use (moderate SOE). Of the 17 studies reporting data on epidural use in births supported by a trained doula, 7 studies^23,26,27,30,35,39,44^ reported significantly lower rates of epidural use, and the remaining 10 studies^24,31–34,36,40,42,43,45,62^ reported lower but nonsignificant differences in rates of epidural use between doula-supported compared with non-doula-supported groups.

It is unclear whether a layperson as doula support impacts epidural use. A single RCT set in Thailand^61^ was identified and reported no significant difference in epidural use with layperson doula support (insufficient SOE).

##### Labor Pain

Trained doula support may be associated with reduced labor pain, but our confidence in these findings is low (low SOE), as they are based on a small number of studies (N = 5) with considerable methodological limitations. One study excluded a high number of potential participants based on intention to use formula versus breast milk postpartum^29^ and 2 others had unclear inclusion and allocation protocols.^30,46^ Of the 5 studies^29,30,37,46,47^ that reported labor pain in groups supported by trained doulas, 1 cohort study^29^ demonstrated lower levels of pain (<6 on the Visual Analogue Scale; active phase 3.6 vs 8.8, p < .05) compared with births without trained doula support, and another RCT^47^ reported fewer birthing persons reporting labor pain with trained doula support (36.52% vs 41.72%, p < .001). Three other studies^30,37,46^ reported no significant difference in labor pain ratings between those with and without trained doula support.

Laypersons as doula support may also be associated with reduced labor pain, but similarly, our confidence in these findings is limited (low SOE) based on a small number of studies (N = 3) with consistent reporting of pain reduction in supported groups using different scales and measures of pain assessment. Three studies^54,59,60^ that reported labor pain data found lower levels of pain at the end of active labor among groups supported by a layperson doula. One RCT,^59^ using an untrained companion of the birthing person’s choice, reported a small but significant difference in pain levels between supported and unsupported groups (mean = 6.3, 95% CI [6.1, 6.5] vs 6.9, 95% CI [6.7, 7.1], p < .001). Another RCT^60^ using an untrained female friend or relative selected by the birthing person for support reported nonsignificant differences in severe pain during the start of active labor among 8 patients, but reported significantly fewer reports of severe labor pain among supported birth compared with unsupported births at the end of active phase (36 doula vs 61 control, p = .001). The third study^54^ did not fully report pain data but reported that the supported group scored 50% lower (nonsignificant) on the McGill Pain Rating Index compared with the unsupported control group.

##### Duration of Labor

Trained doula support is likely associated with shorter duration of labor, based on 14 studies consistently reporting shorter labor duration (moderate SOE). Of the 14 studies reporting on duration of labor, 8 reported shorter labor times^22,24,26,27,37–39,52^ in the supported group with trained doula support, 4 studies (in 5 publications)^29,31,42,43,51,62^ reported shorter but nonsignificant differences between groups, and 1 cohort study set in Taiwan^25^ reported longer total labor duration among doula supported births, but also higher rates of natural birth (87.0% vs 56.8%) among doula-supported births.

Lay doula support is also likely to be associated with shorter or no difference in duration of labor, based on 6 studies consistently reporting reduction or no difference in labor duration (moderate SOE). Of the 6 studies reporting duration of labor with a layperson as doula support, 3 RCTs^57,59,60^ reported significantly shorter labor durations (p < .05 or better), and 2 studies^54,61^ had nonsignificant differences between supported groups compared with non-doula-supported groups. One cohort study^55^ in hospital settings in Egypt, Lebanon, and Syria reported duration of labor was increased by 30 minutes (p = .001) after implementation of the birth companion model, but consistent with other included studies, the model was associated with significantly lowered cesarean birth rates.

#### Neonatal Outcomes

##### Infant Mortality

It is unclear whether trained doula support impacts infant mortality based on a single observational study directly reporting reduction in infant mortality with some methodological concerns (insufficient SOE). A single observational study^21^ of TBAs affiliated with the Mayan Health Alliance among rural Guatemalan villages observed fewer neonatal deaths among participants supported by TBAs compared to those who were not (6/276 [2.2%] vs 13/571 [2.8%]), although this difference was nonsignificant. Stillbirth rates were slightly higher in the doula-supported group (4/276 [1.5%] vs 0/571 [0%], p = .007). There were no studies identified that reported infant mortality rates among births supported by laypersons as doula.

##### Apgar Score

Trained doula support may or may not be associated with higher 5-minute Apgar scores (normative value = 7 to 10 points^64^). Our confidence in these findings is limited by several studies with mixed findings and using different Apgar cut-off points (low SOE). We identified 16 studies that reported Apgar scores for neonates birthed with trained doula support. Nearly all studies had non-significant differences in Apgar at 1-minute assessment (Apgar of <7 at 1 min) but improved at the 5-minute assessment in both doula supported and non-doula-supported groups (Apgar of <7 at 5 minutes). Five studies^22,24,26,30,36^ reported higher Apgar at 5 minutes among doula-supported births (Apgar of >7 at 5 minutes, p < .05 or better), but one US-based study^30^ employed an Apgar of 9 as a cut-off point instead of the standard value of 7 points. Nine studies^23,25,27,31,38,42,44–46,48,52^ reported no significant differences in Apgar score between doula-supported and non-doula-supported births with variation in whether Apgar scores were better or not between doula-supported and non-doula-supported births.

Laypersons as doula support may be associated with higher Apgar scores (5 min), but our confidence in these findings is limited by a small number of studies (N = 5) with mixed findings and some methodological concerns (low SOE). Of the 5 studies^53–55,58,61^ that reported Apgar scores in neonates birthed with layperson as doula support, 2 studies reported better Apgar scores with support. One South African RCT^54^ utilizing a hospital volunteer as layperson support reported fewer neonates with Apgar score <7 at 1 minute (12/87 [13.8%] vs 22/91 [24.2%], p = 0.08) and non-significant differences at 5 minutes. Another RCT set in India reported Apgar >7 at 5 minutes for nearly all neonates in both groups irrespective of support (4174 (98.8%) vs 4233 (96.8%). Only 1 study^55^ reported lower Apgar scores in layperson-supported births (Apgar score at 5 minutes < 6: 11.6% vs 6.7%, 95% CI [0.03, 0.06], p = .001), although this study was limited by inconsistent adherence to the birth companion intervention and variation in hospital policies for companions in the birth space.

##### Low Birth Weight

Six studies reported fewer or no difference in the number of low birth weight (LBW) neonates with trained doula support with inconsistent classification of LBW (low SOE). Of these, 3 studies^23,35,50^ reported fewer LBW neonates with doula support, and 3 other studies^26,40,49^ found no significant difference in LBW between supported and unsupported births. The definition of low birth weight was not standardized across all studies, but many used ≤2500 grams as a cut-off (normative value > 2500 g, with LBW < 2500 g).^65^ There were no studies identified that reported LBW among births supported by laypersons as doula.

##### NICU Admission

Trained doula support may be associated with lower NICU admission, based on 4 studies (in 5 publications) reporting non-significant differences in NICU admission rates between trained doula support and no support, but with mixed directions of effect (low SOE). NICU admissions were slightly lower in 1 study^49^ and nonsignificant in the other 3 studies (in 4 publications).^26,31,35,62^ Similarly, in 2 studies with layperson doula support,^53,57^ NICU admission rates were lower or not significantly different between those with and without layperson doula support. Our confidence in these findings is limited by a small number of studies (N = 2) with some methodological concerns (low SOE).

### HARMS OF DOULA SUPPORT

No studies were identified that reported harms related to trained doula support or support by laypersons acting as doula.

### IMPLEMENTATION CHARACTERISTICS OF DOULA SUPPORT

No studies directly evaluated the impact of doula support implementation characteristics with maternal, delivery, or neonatal outcomes. Therefore, we were unable to synthesize evidence on successful doula programs. However, 32 studies provided implementation details for doula support, and key components are summarized in Table 2.

One systematic review^66^ examined factors affecting the implementation of birth companions of choice in the labor and delivery space. Overall, the review reported positive experiences for the pregnant individual who was allowed a birthing companion, irrespective of the person providing the support. The most effective interventions were when support was provided by a non-employee of the hospital. Major barriers to implementation included providers’ negative perceptions of the birth companion, lack of resources to facilitate nurses or midwives’ continuous presence with the pregnant person during labor and birth when they were the birthing companion of choice, constraints related to crowding and availability of space and privacy for the birthing family in the labor ward, and cultural preferences of the birthing person and companion.

Table 2 Characteristics of Doula Support

Support Type | Implementation Characteristics
Trained Doula Support ^21^ ^–^ ^26^ ^,^ ^28^ ^–^ ^31^ ^,^ ^33^ ^–^ ^37^ ^,^ ^44^ ^,^ ^45^ ^,^ ^47^ ^–^ ^52^ ^,^ ^62^ | 1:1 labor to delivery support; - Hospital-based certified doula or nurse/midwife with doula training as part of L&D team is assigned to birthing person either at initiation of active labor or at 3 cm dilation; - Stays with birthing person to provide coaching and physical support through delivery
Trained Doula Support ^21^ ^–^ ^26^ ^,^ ^28^ ^–^ ^31^ ^,^ ^33^ ^–^ ^37^ ^,^ ^44^ ^,^ ^45^ ^,^ ^47^ ^–^ ^52^ ^,^ ^62^ | 1:1 start of labor to 2 hours postpartum support; - Hospital-based certified doula or doula-trained nurse/midwife as part of L&D team is assigned to birthing person either at initiation of active labor or at 3 cm dilation; - Stays with birthing person to provide coaching and physical support through delivery; - Provides breast-feeding and lactation support up to 2 hours postpartum
Trained Doula Support ^21^ ^–^ ^26^ ^,^ ^28^ ^–^ ^31^ ^,^ ^33^ ^–^ ^37^ ^,^ ^44^ ^,^ ^45^ ^,^ ^47^ ^–^ ^52^ ^,^ ^62^ | 1:1 Antenatal visits to postpartum support; - Private doula with credentials at hospital, may be part of L&D team, but begins contact with birthing person in the form of antenatal visits either at-home or in the hospital, provides education and works with birthing person on a birth plan while setting expectations for the labor/birthing process; - Works with birthing person to understand requirements/needs/values of birthing person and acts as advocate for them in the delivery room; - Stays with birthing person to provide coaching, emotional, and physical support through delivery; - Provides breastfeeding and lactation support and postpartum visits; - Provides grief support/counseling for birthing person in the case of unexpected birth outcomes or loss of pregnancy; - Doulas often work independently from the hospital system and are specifically hired by the pregnant family. This independence helps keep them aligned with the preferences of their clients, and not influenced by hospital policies if they might go against preferences of the pregnant individual. It allows for advocacy of pregnant person’s values and preferences.
Layperson as Doula Support ^53^ ^–^ ^55^ ^,^ ^58^ ^–^ ^61^ | Family Relative/Friend; - Often a female person of the birthing person’s choice that may have prior experience with labor and childbirth; - May understand cultural or religious requirements/needs/values of birthing person and acts as advocate for them in the delivery room; - Stays with birthing person to provide emotional and physical support through delivery as allowed by hospital policy
Layperson as Doula Support ^53^ ^–^ ^55^ ^,^ ^58^ ^–^ ^61^ | Volunteer; - May be a friend/relative or hospital-based volunteer who stays with birthing person to provide emotional and physical support through delivery; - May or may not have any previous pregnancy or childbirth experience

Abbreviation. L&D=labor and delivery.

## DISCUSSION

This systematic review synthesized evidence on the benefits and harms of doula support initiatives and summarizes program implementation characteristics to inform development of a doula program within the VHA. Included studies suggest that trained doulas could be associated with a reduced rate of cesarean birth, whereas layperson doulas may reduce or have no effect on cesarean rates. We also found evidence that doula care by either trained or lay doulas could reduce or have no association with labor augmentation with oxytocin and reduction in labor pain. Both trained and layperson doula support was associated with shortened duration of labor, whereas only trained doula support appeared to have an association with reduction in epidural use. With respect to neonatal outcomes, included studies suggest possible benefits of doula support on Apgar scores, frequency of low birth weight neonates, and neonatal intensive care unit (NICU) admission, and doula support did not appear to have negative impact.

By categorizing interventions in our review based on doula training level, we hoped to learn how training could affect the above studied outcomes. There was a lack of evidence for a reduction in cesarean rates in the layperson doula intervention group. Otherwise, the positive associations for maternal/delivery outcomes including oxytocin use, duration of labor, and pain perception could be observed in studies with both trained and lay doulas.

Our findings are generally consistent with prior reviews and a meta-analysis on this topic. For example, a 2017 review^15^ explored outcomes of doula support in 27 trials (17 of which were included in the current review) and concluded that doula support was associated with increases in spontaneous vaginal delivery, decreases in cesarean rates, reduced use of intrapartum analgesia, shorter labors, and less likelihood of low 5-minute Apgar scores, with low strength of evidence for each of these findings. A 2015 meta-analysis^16^ of 5 RCTs (all included in this review) found that doula care significantly reduced cesarean rates and reduced instrumental vaginal delivery, an outcome not specifically addressed in the current review. In this review, epidural and oxytocin use was reduced in the doula care group but did not reach statistical significance. Similarly, a 2015 review^67^ of 48 studies found a reduction in cesarean rates, epidural use, and labor augmentation with doula support. Finally, a 2012 AHRQ review^68^ examining strategies to reduce cesarean rates in low-risk pregnant individuals included 4 studies of doula support programs grouped by whether care was delivered by trained doula or lay providers. This review found low strength of evidence to support a reduction in cesarean deliveries with trained doulas and only 1 RCT suggesting a similar reduction with lay providers of doula support.

Synthesizing evidence on how doula care may affect the subjective birthing experience of the mother was beyond the scope of this review. However, findings from a number of qualitative or mixed-methods studies have suggested that doula care can be useful for contributing to the positive experience of the mother, including through offering stability and security throughout the birthing process, increasing self-efficacy, and helping to advocate for the mother’s needs throughout the birthing process.^24,42,69^ These potential benefits may be important in the context of intrapartum care among Veterans, particularly for Veterans with trauma histories or chronic pain. In the same vein, training in trauma-informed care and knowledge of the mental health conditions commonly affecting Veterans could help doulas best support birthing persons’ mental health needs and facilitate referrals to a higher level of care when needed. A list of competencies used by major doula organizations (eg, Doulas of North America and the International Childbirth Education Association)^13,70^ and the birth doula scope of practice is provided in Appendix E.

The increased number of women separating from the armed forces has corresponded with recent legislative actions focusing on maternal and neonatal outcomes among Veterans. In November 2021, the Department of Defense announced a new program that will provide a certified doula and a lactation consultant to assist vaginal or cesarean births under the supervision of an authorized practitioner to users of the Tricare health program at civilian facilities in the US, with a projected expansion internationally by 2025.^71,72^ A similar pilot program will be implemented within the VHA according to the Delivering Optimally Urgent Labor Access for Veterans Affairs Act of 2021 (DOULA Act for VA), and the Protecting Moms Who Served Act of 2021 was recently passed to direct $15 million towards VHA maternity care.

### LIMITATIONS

Inconsistent methodology and design of included studies limits the ability to compare findings across studies, as does the inconsistent and diverse definition of trained labor support, its duration, and the varying quality and scope of doula training. Some studies also did not provide a clear description of how doula programs may have been implemented or relied on retrospective medical record review for presence of support person with no other descriptors on support provided. Wide variation in the type of doula (trained or layperson) and level and timing of doula support interventions reduced our ability to compare outcomes across studies. Additionally, some studies were conducted in developing countries while others were in high-income countries in which the context of birth is very different. Given the scope and purpose of this review, we focused on characteristics of doula support and outcomes of interest without consideration to health care system and health care access.

Limitations of our methods include single review at the abstract screening level and sequential review for study selection, data abstraction, and quality assessment (in contrast to dual independent review for all steps), which could have led to missing eligible studies. Although our scope focused on outcomes of greatest interest to VHA populations, these outcomes did not always align with the outcomes of interest in included studies. For example, in one included cohort study,^55^ a doula program resulted in a significant change in birthing culture and woman-centered care in countries in which labor companionship in hospitals was previously not allowed. In another study,^21^ an increase in cesarean rates among the intervention group was a benefit (rather than an adverse event), as it indicated an increase in appropriate referrals for obstetric care among higher risk pregnant individuals where emergent medical care would not have been possible otherwise.

### RESEARCH IN PROGRESS AND FUTURE RESEARCH

We identified 13 studies in progress (see Appendix F in Supplemental Materials) which examine perinatal birth outcomes or maternal satisfaction outcomes related to continuous labor support utilizing trained doulas. These studies are largely focused on US populations and aim to address issues around health care access and other social determinants of health impacting at-risk civilian pregnant individuals (eg, socioeconomic status, education, incarceration, race, and ethnicity). As noted in a 2018 evidence review conducted by the ESP,^73^ few available research publications examine social determinants impacting health behaviors, health services utilization, and health outcomes for Veterans such as rurality, mental health, trauma, sexual orientation, and gender identity.

In addition, while not specifically described as a harm, some excluded studies^74–76^ reported anecdotal data from provider surveys that described some conflict between practitioners and doulas related to perceptions of obstetric/physician culture compared with natural birth “counter culture.” These studies suggest that such conflict could be perceived as harmful to the birthing environment or contribute to maternal anxiety if the patient is aware of the tension. These studies also reported improvement in working relationships through education about the scope of practice for birth and labor doulas and by clarification of roles on maternity care teams, particularly among staff with overlapping roles (eg, midwives and L&D team members). It may be important for future research and program implementations to include trainings to help ensure buy-in of personnel and reduce biases against doula-provided care.

The most applicable future research for VHA program planning would focus on the services provided by trauma-informed, full-spectrum doula care, as this is the type of model most employed in US settings and most likely to be piloted within the VHA. As noted, we found considerable variation among doula programs and little evidence identifying key program components. Moreover, many study interventions may not be accurate representations of real-world doula care, which is often more comprehensive and longitudinal.^67^ In most studies, pregnant individuals met a doula at the time of presenting to the hospital in labor, whereas many professional doulas’ support is initiated in the prenatal period and continues after birth. Future research and program evaluations that aim to examine critical components and implementation characteristics (eg, timing of doula care initiation, training in trauma-informed care) would help clarify the best doula program model for the VHA context.

### CONCLUSIONS

Available evidence suggests that full-spectrum trained doula support services in the form of continuous support during labor and delivery may be beneficial to birthing individuals. Specifically, we found that this type of support may improve birth (eg, higher 5-minute Apgar scores and reduced NICU admission) and maternal delivery outcomes (eg, reduced need for cesarean, reduced need for Pitocin/oxytocin). We found no evidence of harms of doula support or support by layperson companionship during labor. Evidence on doula support is generally limited by inconsistency in study methodologies and intervention definitions. Future research to identify key program components and optimal intervention characteristics is warranted.

## REFERENCES

1 Women Veterans Task Force. 2012 Report - Strategies for Serving Our Women Veterans. 2012.
2 Mattocks KM, Skanderson M, Goulet JL, . Pregnancy and mental health among women veterans returning from Iraq and Afghanistan. Journal of Women’s Health. 2010;19(12):2159–2166.
3 Council on Foreign Relations. Demographics of the U.S. Military. https://www.cfr.org/backgrounder/demographics-us-military#:~:text=Today%2C%20women%20represent%2016%20percent%20of%20the%20enlisted,inclusive%20force%20that%20attracts%20the%20country%E2%80%99s%20top%20talent (https://www.cfr.org/backgrounder/demographics-us-military#:%7E:text=Today%2C%20women%20represent%2016%20percent%20of%20the%20enlisted,inclusive%20force%20that%20attracts%20the%20country%E2%80%99s%20top%20talent). Published 2020. Accessed 3/1/22.
4 Department of Veteran Affairs. Study of Barriers for Women Veterans to VA Health Care. 2015.
5 Department of Veteran Affairs. Women Veterans Health Care. https://www.womenshealth.va.gov/WOMENSHEALTH/OutreachMaterials/GeneralHealthandWellness/maternity.asp. Published 2022. Accessed.
6 Gray S. UMMS, VA launch first ever VA study of women’s maternal health care. In. Vol 2022. UMass Chan Medical School 2016.
7 Katon J, Mattocks K, Zephyrin L, . Gestational diabetes and hypertensive disorders of pregnancy among women veterans deployed in service of operations in Afghanistan and Iraq. Journal of women’s health. 2014;23(10):792–800.
8 Araneta MRG, Kamens DR, Zau AC, . Conception and pregnancy during the Persian Gulf War: the risk to women veterans. Annals of epidemiology. 2004;14(2):109–116.15018883
9 Nillni YI, Fox AB, Cox K, Paul E, Vogt D, Galovski TE. The impact of military sexual trauma and warfare exposure on women veterans’ perinatal outcomes. Psychol Trauma. 2021.
10 Preliminary Investigation of Outpatient Community Care Use Among Veteran VHA Patients, FY18. Women Veterans in the Veterans Health Administration; 2018. https://www.herc.research.va.gov/files/MPDF_WHEI-FY18-CC-Out-prelim.pdf. Accessed 3/8/2022.
11 National Health Law Center. Building A Successful Program For Medi-Cal Coverage For Doula Care: Findings From A Survey of Doulas in California. 2020.
12 ACOG. Safe Prevention of the Primary Cesarean Delivery. Consensus Statement of the American College of Obstetricians and Gynecologists and the Society for Maternal-Fetal Medicine. 2014.
13 DONA International. Position Paper: The Birth Doula’s Role in Maternity Care. 2016.
14 Caughey AB, Cahill AG, Guise JM, Rouse DJ. Safe prevention of the primary cesarean delivery. Am J Obstet Gynecol. 2014;210(3):179–193.24565430
15 Bohren MA, Hofmeyr GJ, Sakala C, Fukuzawa RK, Cuthbert A. Continuous support for women during childbirth. Cochrane Database of Systematic Reviews. 2017;7:CD003766.28681500
16 Fortier JH, Godwin M. Doula support compared with standard care: Meta-analysis of the effects on the rate of medical interventions during labour for low-risk women delivering at term. Canadian Family Physician. 2015;61(6):e284–e292.
17 PICO Portal. www.picoportal.org. Published 2021. Accessed.
18 Thomson H, Craig P, Hilton-Boon M, Campbell M, Katikireddi SV. Applying the ROBINS-I tool to natural experiments: an example from public health. Systematic Reviews. 2018;7(1):15.29368630
19 Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. 2019;366:l4898.31462531
20 Berkman ND, Lohr KN, Ansari MT, . Grading the strength of a body of evidence when assessing health care interventions: an EPC update. J Clin Epidemiol. 2015;68(11):1312–1324.25721570
21 Austad K, Juarez M, Shryer H, Moratoya C, Rohloff P. Obstetric care navigation: results of a quality improvement project to provide accompaniment to women for facility-based maternity care in rural Guatemala. BMJ Quality & Safety. 2020;29(2):169–178.
22 Bolbol-Haghighi N, Masoumi SZ, Kazemi F. Effect of Continued Support of Midwifery Students in Labour on the Childbirth and Labour Consequences: A Randomized Controlled Clinical Trial. Journal of Clinical and Diagnostic Research JCDR. 2016;10(9):QC14–QC17.
23 Byrskog U, Small R, Schytt E. Community-based bilingual doulas for migrant women in labour and birth - findings from a Swedish register-based cohort study. BMC Pregnancy & Childbirth. 2020;20(1):721.33228571
24 Campbell DA, Lake MF, Falk M, Backstrand JR. A randomized control trial of continuous support in labor by a lay doula. J Obstet Gynecol Neonatal Nurs. 2006;35(4):456–464.
25 Chen CC, Lee JF. Effectiveness of the doula program in Northern Taiwan. Tzuchi Medical Journal. 2020;32(4):373–379.
26 Cogan R, Spinnato JA. Social support during premature labor: effects on labor and the newborn. Journal of Psychosomatic Obstetrics & Gynecology. 1988;8(3):209–216.
27 Dickinson JE, Paech MJ, McDonald SJ, Evans SF. The impact of intrapartum analgesia on labour and delivery outcomes in nulliparous women. Australian and New Zealand journal of obstetrics and gynaecology. 2002;42(1):65–72.
28 Dundek LH. Establishment of a Somali doula program at a large metropolitan hospital. Journal of Perinatal & Neonatal Nursing. 2006;20(2):128–137.16714912
29 Feng BB, Wang L, Zhai JJ. Investigation on delivery analgesia effect of combined spinal epidural anesthesia plus Doula and safety of mother and baby. Clinical & Experimental Obstetrics & Gynecology. 2013;40(4):574–578.24597260
30 Fulton JM. Doula Supported Childbirth: An Exploration of Maternal Sensitivity, Self-Efficacy, Responsivity, and Parental Attunement, University of California, Davis; 2011.
31 Gagnon AJ, Waghorn K, Covell C. A randomized trial of one-to-one nurse support of women in labor. Birth. 1997;24(2):71–77.9271971
32 Goedkoop V. Side by side -- a survey of doula care in the UK in 2008. MIDIRS Midwifery Digest. 2009;19(2):217–218.
33 Gordon NP, Walton D, McAdam E, Derman J, Gallitero G, Garrett L. Effects of providing hospital-based doulas in health maintenance organization hospitals. Obstetrics & Gynecology. 1999;93(3):422–426.10074992
34 Gruber KJ, Cupito SH, Dobson CF. Impact of doulas on healthy birth outcomes. Journal of Perinatal Education. 2013;22(1):49–58.24381478
35 Hans SL, Edwards RC, Zhang Y. Randomized Controlled Trial of Doula-Home-Visiting Services: Impact on Maternal and Infant Health. Maternal & Child Health Journal. 2018;22(Suppl 1):105–113.29855838
36 Hodnett ED, Lowe NK, Hannah ME, . Effectiveness of nurses as providers of birth labor support in North American hospitals: a randomized controlled trial. JAMA. 2002;288(11):1373–1381.12234231
37 Isbir GG, Sercekus P. The Effects of Intrapartum Supportive Care on Fear of Delivery and Labor Outcomes: A Single-Blind Randomized Controlled Trial. Journal of Nursing Research. 2017;25(2):112–119.
38 Kashanian M, Javadi F, Haghighi MM. Effect of continuous support during labor on duration of labor and rate of cesarean delivery. International Journal of Gynecology & Obstetrics. 2010;109(3):198–200.20152972
39 Kennell J, Klaus M, McGrath S, Robertson S, Hinkley C. Continuous emotional support during labor in a US hospital. A randomized controlled trial. JAMA. 1991;265(17):2197–2201.2013951
40 Kozhimannil. Doula care, birth outcomes, and costs among Medicaid beneficiaries. 2013.
41 Kozhimannil KB, Attanasio LB, Jou J, Joarnt LK, Johnson PJ, Gjerdingen DK. Potential benefits of increased access to doula support during childbirth. American Journal of Managed Care. 2014;20(8):e340–352.25295797
42 Langer A, Campero L, Garcia C, Reynoso S. Effects of psychosocial support during labour and childbirth on breastfeeding, medical interventions, and mothers’ wellbeing in a Mexican public hospital: a randomised clinical trial. British Journal of Obstetrics & Gynaecology. 1998;105(10):1056–1063.9800927
43 Lesser PA, Maurer M, Stephens S, Yolkut R. Doulas for all. International Journal of Childbirth Education. 2005;20(3):28–32.
44 McGrath SK, Kennell JH. A randomized controlled trial of continuous labor support for middle-class couples: effect on cesarean delivery rates. Birth. 2008;35(2):92–97.18507579
45 Mottl-Santiago J, Walker C, Ewan J, Vragovic O, Winder S, Stubblefield P. A hospital-based doula program and childbirth outcomes in an urban, multicultural setting. In. Maternal & Child Health Journal. Vol 122008:372–377.
46 Nommsen-Rivers LA, Mastergeorge AM, Hansen RL, Cullum AS, Dewey KG. Doula care, early breastfeeding outcomes, and breastfeeding status at 6 weeks postpartum among low-income primiparae. J Obstet Gynecol Neonatal Nurs. 2009;38(2):157–173.
47 Ravangard R, Basiri A, Sajjadnia Z, Shokrpour N. Comparison of the Effects of Using Physiological Methods and Accompanying a Doula in Deliveries on Nulliparous Women’s Anxiety and Pain: A Case Study in Iran. Health Care Manager. 2017;36(4):372–379.28961642
48 Shalev J. Having a doula during labor and delivery. Midwifery Today & Childbirth Education. 1992(24):8–9.
49 Spiby H, Green, J. M., Darwin, Z., Willmot, H., Knox, D., McLeish, J., & Smith, M. Multisite implementation of trained volunteer doula support for disadvantaged childbearing women: a mixed-methods evaluation. Centre for Reviews and Dissemination. 2015.
50 Thomas MP, Ammann G, Brazier E, Noyes P, Maybank A. Doula Services Within a Healthy Start Program: Increasing Access for an Underserved Population. Maternal & Child Health Journal. 2017;21(Suppl 1):59–64.29198051
51 Trueba G, Contreras C, Velazco MT, Lara EG, Martinez HB. Alternative strategy to decrease cesarean section: support by doulas during labor. Journal of Perinatal Education. 2000;9(2):8–13.17273201
52 Zhang Y, Johnston L, Ma D, Wang F, Zheng X, Xu X. An exploratory study of the effect of labor pain management on postpartum depression among Chinese women. Ginekologia Polska. 2018;89(11):627–636.30508215
53 Gadappa SN, Deshpande SS. A Quasi-Experimental Study to Compare the Effect of Respectful Maternity Care Using Intrapartum Birth Companion of Her Choice on Maternal and Newborn Outcome in Tertiary Care Centre. Journal of Obstetrics & Gynaecology of India. 2021;71(Suppl 2):84–89.34924719
54 Hofmeyr GJ, Nikodem VC, Wolman W-L, Chalmers BE, Kramer T. Companionship to modify the clinical birth environment: effects on progress and perceptions of labour, and breastfeeding. BJOG: An International Journal of Obstetrics & Gynaecology. 1991;98(8):756–764.
55 Kabakian-Khasholian T, Bashour H, El-Nemer A, Kharouf M, Elsheikh O, Labour Companionship Study G. Implementation of a labour companionship model in three public hospitals in Arab middle-income countries. Acta Paediatrica. 2018;107 Suppl 471:35–43.30570794
56 KC A, Axelin A, Litorp H, Tinkari BS, Sunny AK, Gurung R. Coverage, associated factors, and impact of companionship during labor: A large-scale observational study in six hospitals in Nepal. Birth. 2020a;47(1):80–88.31765037
57 Klaus MH, Kennell JH, Robertson SS, Sosa R. Effects of social support during parturition on maternal and infant morbidity. British Medical Journal Clinical Research Ed. 1986;293(6547):585–587.3092934
58 Madi BC, Sandall J, Bennett R, MacLeod C. Effects of female relative support in labor: a randomized controlled trial. Birth. 1999;26(1):4–8.10352048
59 Morhason-Bello IO, Adedokun BO, Ojengbede OA. Social support during childbirth as a catalyst for early breastfeeding initiation for first-time Nigerian mothers. International Breastfeeding Journal. 2009;4:7p–7p.19607695
60 Safarzadeh A, Beigi M, Salehian T, Khojasteh F, Burayri T, Navabirigi S. Effect of doula support on labour pain and outcomes in primiparous women in Zahedan, southeastern Iran: a randomized controlled trial. J Pain Relief. 2012;1(5):2167-0846.1000112.
61 Yuenyong S, O’Brien B, Jirapeet V. Effects of labor support from close female relative on labor and maternal satisfaction in a Thai setting. J Obstet Gynecol Neonatal Nurs. 2012;41(1):45–56.
62 Gagnon AJ, Waghorn K. One-to-one nurse labor support of nulliparous women stimulated with oxytocin. J Obstet Gynecol Neonatal Nurs. 1999;28(4):371–376.
63 Shelp A. Women helping women: the Somali Doula Initiative. International Journal of Childbirth Education. 2004;19(4):4–7.
64 ACOG. Committee Opinion #644: The Apgar Score. https://www.acog.org/clinical/clinical-guidance/committee-opinion/articles/2015/10/the-apgar-score. Published 2015. Accessed.
65 Cutland CL, Lackritz EM, Mallett-Moore T, . Low birth weight: Case definition & guidelines for data collection, analysis, and presentation of maternal immunization safety data. Vaccine. 2017;35(48 Pt A):6492–6500.29150054
66 Kabakian-Khasholian T, Portela A. Companion of choice at birth: factors affecting implementation. BMC Pregnancy and Childbirth. 2017;17(1):265.28854903
67 Steel A, Frawley J, Adams J, Diezel H. Trained or professional doulas in the support and care of pregnant and birthing women: a critical integrative review. Health & Social Care in the Community. 2015;23(3):225–241.24942339
68 Hartmann KE, Andrews JC, Jerome RN, . Agency for Healthcare Research and Quality. 2012;12(13):10.
69 Lundgren I. Swedish women’s experiences of doula support during childbirth. Midwifery. 2010;26(2):173–180.18639959
70 ICEA. Certification Information,. https://icea.org/certification/icea-certification-philosophy-and-programscertification/. Published 2022. Accessed.
71 Military.com. Tricare Maternity Care For Active Duty and Separating Families. https://www.military.com/benefits/tricare/tricare-maternity-care-options.html#:~:text=Active%20duty%20service%20members%20are%20expected%20to%20receive,a%20local%20civilian%20hospital%20for%20the%20actual%20delivery (https://www.military.com/benefits/tricare/tricare-maternity-care-options.html#:%7E:text=Active%20duty%20service%20members%20are%20expected%20to%20receive,a%20local%20civilian%20hospital%20for%20the%20actual%20delivery). Published 2022. Accessed.
72 Veterans Authority. Pilot Program For Tricare to Cover Doulas, Lactation Consultants Begin. 2021.
73 Duan-Porter W, Martinson BC, Greer N, . Evidence Review—Social Determinants of Health for Veterans. J Gen Intern Med. 2018;33(10):1785–1795.30030735
74 Neel K, Goldman R, Marte D, Bello G, Nothnagle MB. Hospital-based maternity care practitioners’ perceptions of doulas. Birth. 2019;46(2):355–361.30734958
75 Summerton JV, Mtileni TR, Moshabela ME. Experiences and perceptions of birth companions supporting women in labour at a District Hospital in Limpopo, South Africa. Curationis. 2021;44(1):e1–e7.
76 Bohren MA, Berger BO, Munthe-Kaas H, Tuncalp O. Perceptions and experiences of labour companionship: a qualitative evidence synthesis. Cochrane Database of Systematic Reviews. 2019;3:CD012449.30883666

## Supplemental Materials

Download Supplemental Materials PDF

### APPENDIX A SEARCH STRATEGY

#### SYSTEMATIC REVIEWS

Search for current systematic reviews (limited to last 7 years); Date Searched: 01/05/2022
A. Bibliographic Databases: | # | Search Statement | Results
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to January 04, 2022 | 1 | Doulas/ OR (doula$1 OR (labo?r adj1 (coach* OR companion$1)) OR (birth* adj1 (coach* OR companion$1))).mp. | 558
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to January 04, 2022 | 2 | (systematic review.ti. or meta-analysis.pt. or meta-analysis.ti. or systematic literature review.ti. or this systematic review.tw. or pooling project.tw. or (systematic review.ti,ab. and review.pt.) or meta synthesis.ti. or meta-analy*.ti. or integrative review.tw. or integrative research review.tw. or rapid review.tw. or umbrella review.tw. or consensus development conference.pt. or practice guideline.pt. or drug class reviews.ti. or cochrane database syst rev.jn. or acp journal club.jn. or health technol assess.jn. or evid rep technol assess summ.jn. or jbi database system rev implement rep.jn. or (clinical guideline and management).tw. or ((evidence based.ti. or evidence-based medicine/ or best practice*.ti. or evidence synthesis.ti,ab.) and (((review.pt. or diseases category/ or behavior.mp.) and behavior mechanisms/) or therapeutics/ or evaluation studies.pt. or validation studies.pt. or guideline.pt. or pmcbook.mp.)) or (((systematic or systematically).tw. or critical.ti,ab. or study selection.tw. or ((predetermined or inclusion) and criteri*).tw. or exclusion criteri*.tw. or main outcome measures.tw. or standard of care.tw. or standards of care.tw.) and ((survey or surveys).ti,ab. or overview*.tw. or review.ti,ab. or reviews.ti,ab. or search*.tw. or handsearch.tw. or analysis.ti. or critique.ti,ab. or appraisal.tw. or (reduction.tw. and (risk/ or risk.tw.) and (death or recurrence).mp.)) and ((literature or articles or publications or publication or bibliography or bibliographies or published).ti,ab. or pooled data.tw. or unpublished.tw. or citation.tw. or citations.tw. or database.ti,ab. or internet.ti,ab. or textbooks.ti,ab. or references.tw. or scales.tw. or papers.tw. or datasets.tw. or trials.ti,ab. or meta-analy*.tw. or (clinical and studies).ti,ab. or treatment outcome/ or treatment outcome.tw. or pmcbook.mp.))) not (letter or newspaper article).pt. | 493747
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to January 04, 2022 | 3 | 1 and 2 | 33
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to January 04, 2022 | 4 | limit 3 to english language | 32
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to December 28, 2021 | 1 | Doulas.kw. or (doula$1 or (labo?r adj1 (coach* or companion$1)) or (birth* adj1 (coach* or companion$1))).mp. | 20

Search for current systematic reviews (limited to last 7 years); Date Searched: 01/05/2022
B. Non-bibliographic databases | Evidence | Results
AHRQ: evidence reports, technology assessments, U.S Preventative Services Task Force Evidence Synthesis | http://www.ahrq.gov/research/findings/evidence-based-reports/search.html; Search: doula | 0
CADTH | https://www.cadth.ca; Search: doula | 0
ECRI Institute | https://guidelines.ecri.org/; Search: doula | 0
HTA: Health Technology Assessments (UP TO 2016) | http://www.ohsu.edu/xd/education/library/; See CDSR search above | 0
NHS Evidence | http://www.evidence.nhs.uk/default.aspx; Search: doula, limit Secondary Evidence | 39
EPPI-Centre | http://eppi.ioe.ac.uk/cms/Default.aspx?tabid=62; Use browser search function [CNTL + F] for keyword search; Search: doula | 0
NLM | http://www.ncbi.nlm.nih.gov/books; Search: doula; Spiby H, Green JM, Darwin Z, . Multisite implementation of trained volunteer doula support for disadvantaged childbearing women: a mixed-methods evaluation. Southampton (UK): NIHR Journals Library; 2015 Mar. (Health Services and Delivery Research, No. 3.8.) https://www.ncbi.nlm.nih.gov/books/NBK280017/?term=doula; Morrell CJ, Sutcliffe P, Booth A, . A systematic review, evidence synthesis and meta-analysis of quantitative and qualitative studies evaluating the clinical effectiveness, the cost-effectiveness, safety and acceptability of interventions to prevent postnatal depression. Southampton (UK): NIHR Journals Library; 2016 May. (Health Technology Assessment, No. 20.37.). https://www.ncbi.nlm.nih.gov/books/NBK361846/?term=doula | 2
VA Products - VATAP, PBM and HSR&D publications | A. http://www.hsrd.research.va.gov/research/default.cfm; B. http://www.research.va.gov/research_topics/; Search: doula | 0

#### PRIMARY STUDIES

Search for primary literature; Date searched: 01/05/2022
MEDLINE [Ovid MEDLINE(R) ALL 1946 to January 04, 2022]
# | Search Statement | Results
1 | Doulas/ OR (doula$1 OR (labo?r adj1 (coach* OR companion$1)) OR (birth* adj1 (coach* OR companion$1))).mp. | 558

CINAHL [EBSCO CINAHL Plus with Full Text]
# | Search Statement | Results
1 | (MH “Doulas”) | 809
2 | doula OR doulas OR (labo?r N1 (coach* OR companion*)) OR (birth* N1 (coach* OR companion*)) | 1211
3 | 1 OR 2 | 1211
4 | limit 3 to English language | 1187

### APPENDIX B EXCLUDED STUDIES

Exclude reasons: E1=Ineligible population, E2=Ineligible intervention, E3=Ineligible comparator, E4=Ineligible outcome, E5=Ineligible timing, E6=Ineligible study design, E7=Ineligible publication type, E8=Outdated or ineligible systematic review, E9=non-English, E10=Unable to retrieve.

Citation | Exclude Reason
Abramson R, Breedlove G, Isaacs B. Birthing support and the community-based doula. Zero to Three. 2007. p. 55–60. | E10
Abramson R. The critical moment and the passage of time: reflections on community-based doula support. Int J Childbirth Educ. 2004;19(4):34–35. | E7
Adams C, Curtin-Bowen M. Countervailing powers in the labor room: The doula-doctor relationship in the United States. Soc Sci Med. 2021;285:114296.34365071 | E7
Adams ED, Bianchi AL. A practical approach to labor support. J Obstet Gynecol Neonatal Nurs. 2008;37(1):106–15. | E7
Afulani P, Kusi C, Kirumbi L, Walker D. Companionship during facility-based childbirth: results from a mixed-methods study with recently delivered women and providers in Kenya. BMC Pregnancy Childbirth. 2018;18(1). doi:10.1186/s12884-018-1806-1 | E4
Agoratus L. Improving Pregnancy Outcomes For Families: Model Programs Of The Span Parent Advocacy Network. Exceptional Parent. 2018;48(8):32–33. | E7
AHC Media. Labor of love: doula care helps new moms. Women’s Health Center Management. Atlanta, Georgia: AHC Media; 1997. p. 11–13. | E10
AHC Media. Newborn home care can improve outcomes and expand services. Hospital Home Health. 2005;22(4):37–40. | E10
Ahlemeyer J, Mahon S. Doulas for childbearing women. MCN Am J Matern Child Nurs. 2015;40(2):122–7.25723797 | E7
Ahmad N, Syed Nor SF, Daud F. Understanding Myths in Pregnancy and Childbirth and the Potential Adverse Consequences: A Systematic Review. Malaysian J Med Sci. 2019;26(4):17–27. | E6
Akbarzadeh M, Masoudi Z, Zare N, Vaziri F. Comparison of the effects of doula supportive care and acupressure at the BL32 point on the mother’s anxiety level and delivery outcome. Iranian J Nurs Midwifery Res. 2015;20(2):239–46. | E4
Akhavan S, Edge D. Foreign-born women’s experiences of Community-Based Doulas in Sweden--a qualitative study. . Health Care Women Int. 2012a;33(9):833–48.22891742 | E4
Akhavan S, Lundgren I. Midwives’ experiences of doula support for immigrant women in Sweden--a qualitative study. Midwifery. 2012b;28(1):80–5.21236529 | E2
Allen J. Doulas create birth memories worth cherishing.: Canadian Women’s Health Network; 2003. p. 6–7. | E10
Anderson T. Support in labour. Modern Midwife. 1996;6(1):7–11. | E10
Anonymous. Doula project boosted with government funding. Practising Midwife. 2009;12(6):10–10.19437906 | E7
Anonymous. Doulas lend support in times of need. GENESIS. Fall2001 2001;(3):5–5. | E7
Anonymous. Doulas may indicate failings in patient care, warns doctor. Practising Midwife. 2010;13(1):8–8. | E7
Anonymous. Mind over matter: minimising the pain of labour…Mind over matter: minimising the pain of labour (Midwives 2011 7:20-1). Midwives. 2012;15(1):6–6.24877262 | E7
Anonymous. Operation Doula Care: reaching out to military families in North Carolina. GENESIS. 2005;(2):3–3. | E7
Attanasio LB, DaCosta M, Kleppel R, Govantes T, Sankey HZ, Goff SL. Community Perspectives on the Creation of a Hospital-Based Doula Program. Health Equity. 2021;5(1):545–553.34909521 | E4
Bainbridge J. Doulas: supportive, calm birth partners or obstructive to clinicians? Br J Midwifery. 2010;18(1):57–57. | E7
Bareford CG. Commentary on Social support during labor: a community based study [original article by Pascoe J appears in PUBLIC HEALTH NURS 1993;10(2):97-9]. AWHONN’s Women’s Health Nursing Scan. 1993;7(6):10–10. | E7
Barron SP, Lane HW, Hannan TE, Struempler B, Williams JC. Factors influencing duration of breast feeding among low-income women. J Am Dietetic Assoc. 1988. p. 1557–61. | E7
Bar-Yam NB. Political issues. Doula care: an age-old practice meets the 21st century. Int J Childbirth Educ. 2003;18(4):18–21. | E7
Basile Ibrahim B, Knobf MT, Shorten A, . “I had to fight for my VBAC”: A mixed methods exploration of women’s experiences of pregnancy and vaginal birth after cesarean in the United States. Birth: Issues in Perinatal Care. 2021;48(2):164–177. doi:10.1111/birt.12513 | E4
Behnke EF, Hans SL. Becoming a doula. Zero to Three. 2002;23(2):9–13. | E7
BenZion M. Learning to Trust Birth through Continuity of Care. Midwifery Today. 2018;(125):18–22. | E7
Berbyuk Lindstrom N, Rodriguez Pozo R. Perspectives of Nurses and Doulas on the Use of Information and Communication Technology in Intercultural Pediatric Care: Qualitative Pilot Study. JMIR Pediatrics and Parenting. 2020;3(1):e16545.32181748 | E4
Berg M, Terstad A. Swedish women’s experiences of doula support during childbirth. Midwifery. 2006;22(4):330–8.16603283 | E4
Berghella V, Baxter JK, Chauhan SP. Evidence-based labor and delivery management. Am J Obstet Gynecol 2008. p. 445–54.18984077 | E8
Berghella V, Di Mascio D. Evidence-based labor management: before labor (Part 1). Review. Am J Obstet Gynecol MFM. 2020;2(1):100080.33345992 | E7
Betrán AP, Temmerman M, Kingdon C, . Interventions to reduce unnecessary caesarean sections in healthy women and babies. Lancet. 2018;392(10155):1358–1368. doi:10.1016/S0140-6736(18)31927-5 30322586 | E7
Bevinetto G. Lean on me: having a doula at the birth…Debra Pascali-Bonaro. American Baby. 2003;65(8):41–42. | E10
Bharti J, Kumari A, Zangmo R, Mathew S, Kumar S, Sharma AK. Establishing the practice of birth companion in labour ward of a tertiary care centre in India-a quality improvement initiative. BMJ Open Quality. 2021;10(Suppl 1):07. | E4
Bhutta ZA, Darmstadt GL, Haws RA, Yakoob MY, Lawn JE. Delivering interventions to reduce the global burden of stillbirths. Neonatal Intensive Care. 2009;22(7):39–43. | E2
Bianchi AL, Adams ED. Doulas, labor support, and nurses. Int J Childbirth Educ. 2004;19(4):24–30. | E7
Biggs S, Keon J, Singer O, . Question of the quarter. Q: What are the essential elements of good prenatal care? Midwifery Today. 2001;(59):8–68. | E7
Birth Issues. Continuous labour support offers big benefits to mothers & babies: support from non-hospital caregivers reduced risk of caesarean birth by impressive 26%. Birth Issues; 2003. p. 24–27. | E7
Bohren MA, Berger BO, Munthe-Kaas H, Tuncalp O. Perceptions and experiences of labour companionship: a qualitative evidence synthesis. Cochrane Database Syst Rev. 2019;3:CD012449.30883666 | E4
Bower K, Jordan B, VanZandt S. A birthing buddy: emotional care during childbirth. Nursing Spectrum -- Washington DC & Baltimore Edition. 2003a;13(13):11–11. | E10
Bower K, Van Zandt S, Jordan B. Birth companions at JHU. Nursing Spectrum -- Washington DC & Baltimore Edition. 2003b;13(15):4–4. | E7
Bowers BB. Mothers’ experiences of labor support: exploration of qualitative research. J Obstet Gynecol Neonatal Nurs. 2006;31(6):742–52. | E6
Breedlove G. Perceptions of social support from pregnant and parenting teens using community-based doulas. J Perinatal EducEd. 2005. p. 15–22. | E10
Breedlove GK. A description of social support and hope in pregnant and parenting teens receiving care from a doula. University of Missouri - Kansas City; 2001. | E4
Brigstocke S. What really happens during birth and how can a doula help? J Holistic Healthcare.2017;14(2):14–16. | E7
Brisco CM, Small SP. Doula Support During Childbearing--Aiming for the Best Birthing Experience: A Phenomenological Study. International Journal of Childbirth. 2017;7(3):139–151. doi:10.1891/2156-5287.7.3.139 | E4
British Homeopathic Association. Mum’s the word. Health & Homeopathy. Spring/Summer2019 2019:19–21. | E10
Bromberg SR, Frankel K. Perinatal support in substance abuse: the requirements of relationship and reflection. Zero to Three. 2009;29(4):22–27. | E4
Brown C. Focal point on labor support: pregnancy and labor support for the high-risk woman. Int J Childbirth Educ. 2001;16(2):24–27. | E4
Brown CE. Unexpected outcomes in the childbearing cycle: how the doula and childbirth educator can help at the time of crisis. Int J Childbirth Educ. 2000;15(3):32–33. | E7
Bruggemann OM, Osis MJ, Parpinelli MA. [Support during childbirth: perception of health care providers and companions chosen by women]. Randomized Controlled Trial. Revista de Saude Publica. 2007;41(1):44–52.17273633 | E9
Bruggemann OM, Parpinelli MA, Osis MJ. [Evidence on support during labor and delivery: a literature review]. Cadernos de Saude Publica. 2005;21(5):1316–27.16158136 | E9
Burch JK, J. What are the views of women and healthcare providers regarding labor companions during childbirth? Cochrane Clinical Answers. 2019/09/09 2019; | E7
Burgess A. An Evolutionary Concept Analysis of Labor Support. Int J Childbirth Educ. 2014;29(2):64–72. | E4
Campbell D, Scott KD, Klaus MH, Falk M. Female relatives or friends trained as labor doulas: outcomes at 6 to 8 weeks postpartum. Birth. 2007;34(3):220–7.17718872 | E4
Campbell-Voytal K, Fry McComish J, Visger JM, Rowland CA, Kelleher J. Postpartum doulas: motivations and perceptions of practice. Midwifery. 2010;27(6):e214–21.21055853 | E4
Campero L, Garcia C, Diaz C, Ortiz O, Reynoso S, Langer A. “Alone, I wouldn’t have known what to do”: a qualitative study on social support during labor and delivery in Mexico. Soc Sci Med. 1998;47(3):395–403.9681909 | E4
Cattelona G, Friesen CA, Hormuth LJ. The Impact of a Volunteer Postpartum Doula Program on Breastfeeding Success: A Case Study. Journal of Human Lactation. 2015;31(4):607–10.25900845 | E7
Chalmers B, Wolman W. Social support in labor--a selective review. Journal of Psychosomatic Obstetrics & Gynecology. 1993;14(1):1–15. | E9
Chang YS, Coxon K, Portela AG, Furuta M, Bick D. Interventions to support effective communication between maternity care staff and women in labour: A mixed-methods systematic review. Midwifery. 2018;59:4–16.29351865 | E2
Chapple W, Gilliland A, Li D, Shier E, Wright E. An economic model of the benefits of professional doula labor support in Wisconsin births. WMJ. 2013;112(2):58–64.23758016 | E6
Chee A. A birth doula for every mother. Midwifery Today with International Midwife. 2012;(104):21–3. | E7
Chi PC, Urdal H. The evolving role of traditional birth attendants in maternal health in post-conflict Africa: A qualitative study of Burundi and northern Uganda. SAGE Open Medicine. 2018;6:. | E4
Choi Myung S, Kim Gum J. Effects of Paters’ Duola Touch during Labor on the Paternal Attachment and Role Confidence to Neonate and Couple Attachment. Korean Journal of Women Health Nursing. 2011;17(4):426–437. doi:10.4069/kjwhn.2011.17.4.426 | E9
Claudio E, Donahue J, Niles PM, . Mobilizing a Public Health Response: Supporting the Perinatal Needs of New Yorkers During the COVID-19 Pandemic. Mat Child Health J. 2020;24(9):1083–1088. doi:10.1007/s10995-020-02984-6. | E4
Collins CC, Rice H, Bai R, Brown PL, Bronson C, Farmer C. “I felt like it would’ve been perfect, if they hadn’t been rushing”: Black women’s childbirth experiences with medical providers when accompanied by perinatal support professionals. J Advanced Nurs. 2021;77(10):4131–4141. | E4
Conrad M, Stricker S. Personality and labor: a retrospective study of the relationship between personality traits and birthing experiences. Journal of Reproductive & Infant Psychology. 2017;36(1):67–80.29517297 | E4
Culley C. Postpartum Doula Support: Filling a Gap in Maternity Care. RN Idaho. 2020;43(2):13–13. | E7
da Matta Machado Fernandes L, Lansky S, Reis Passos H, C TB, B AS. Brazilian women’s use of evidence-based practices in childbirth after participating in the Senses of Birth intervention: A mixed-methods study. PLoS ONE. 2021;16(4):e0248740.33861756 | E4
Dahl CM, Geynisman-Tan JM, Premkumar A. Birth Behind Bars: The Need for Labor Support in the Incarcerated Population. Obstet Gyn. 2020;136(5):1036–1039. | E4
Dames N, White S. One progressive hospital-based Doula program in a small central California town. Int J Childbirth Educ. Summer98 1998;13(2):6–8. | E4
Darwin Z, Green J, McLeish J, Willmot H, Spiby H. Evaluation of trained volunteer doula services for disadvantaged women in five areas in England: women’s experiences. Evaluation Study. Health Soc Care Community. 2017;25(2):466–477.26918879 | E4
Davis-Floyd R, Gutschow K, Schwartz DA. Pregnancy, Birth and the COVID-19 Pandemic in the United States. Med Anthro. 2020;39(5):413–427. | E4
de Oliveira ASS, Rodrigues DP, Guedes MVC, Felipe GF, de Galiza FT, Monteiro LC. THE COMPANION DURING LABOUR AND BIRTH: NEW MOTHERS’ PERCEPTIONS. Cogitare Enfermagem. 2011;16(2):247–253. | E9
Declercq ER, Sakala C, Corry MP, Applebaum S, Herrlich A. Major Survey Findings of Listening to MothersSM III: Pregnancy and Birth. J Perinatal Educ. 2014;23(1):9–16. doi:10.1891/1058-1243.23.1.9 | E4
Dodson A. The Military Birth Resource Network: Serving Those Who Serve. Midwifery Today. 2018;(127):36–36. | E7
Donegan T. The labour doula. Singapore Nurs J. 2005;32(2):49–50. | E4
dos Santos Moura NA, Rolim de Holanda V, Pereira Melo de Albuquerque G, de Lima Castro JF, de Lira Silva HR, Gomes da Rocha EP. Analysis of practices in childbirth and postpartum hospital care. Rev Rene. 2020;21(1):1–8. doi:10.15253/2175-6783.20202143671 | E4
Dunne CL, Fraser J, Gardner GE. Women’s perceptions of social support during labour: development, reliability and validity of the Birth Companion Support Questionnaire. Midwifery. 2014;30(7):847–52.24290195 | E2
Dynes MM, Binzen S, Twentyman E, . Client and provider factors associated with companionship during labor and birth in Kigoma Region, Tanzania. Midwifery. 2019;69:92–101.30453122 | E4
Edwards RC, Thullen MJ, Korfmacher J, Lantos JD, Henson LG, Hans SL. Breastfeeding and complementary food: randomized trial of community doula home visiting. Pediatrics. 2013;132 Suppl 2:S160–6. | E4
Eftekhary S, Klein MC, Xu SY. The life of a Canadian doula: successes, confusion, and conflict. J Obstet Gyn Can. 2010;32(7):642–9. | E4
Esenalp S, Çoker H. Of Deliveries and Doulas in Turkey. Midwifery Today. Spring2018 2018;(125):35–36. | E4
Essentially MIDIRS. Reducing caesareans in ‘low-risk’ women. Essentially MIDIRS. 2013;4(3):25–25. | E10
Essentially MIDIRS. Update on: support in labour part 2. Essentially MIDIRS. 2011;2(5):39–42. | E10
Fathi Najafi T, Latifnejad Roudsari R, Ebrahimipour H. The best encouraging persons in labor: A content analysis of Iranian mothers’ experiences of labor support. PLoS ONE 2017;12(7):e0179702.28683112 | E4
Felsenthal R. As they grow: pregnancy & birth. A doula delivery. Parents. 2006;81(2):117–118. | E4
Fink JLW. Consult stat. Coordinate patient care when you’re working with a doula. RN. 2005;68(12):61–2p.16128435 | E7
Frank GJ, Swan ML. Doula support for women who are Asylum Seekers or Refugees. Australian Midwifery News. 2016;16(1):34–36. | E7
Froggé GM. Supporting Pregnant Incarcerated Women: Through Childbirth Educational Perspectives. Int J Childbirth Educ. 2019;34(2):51–53. | E4
Garces A, McClure EM, Espinoza L, . Traditional birth attendants and birth outcomes in low-middle income countries: A review. Sem Perinat. 2019;43(5):247–251. | E6
Gentry QM, Nolte KM, Gonzalez A, Pearson M, Ivey S. “Going beyond the call of doula”: a grounded theory analysis of the diverse roles community-based doulas play in the lives of pregnant and parenting adolescent mothers. J Perinatal Educ. 2010;19(4):24–40. | E4
Giangregorio N. Hospital-Based Doula Program. J Obstet Gynecol Neonatal Nurs. 2016;45:S10–S11. doi:10.1016/j.jogn.2016.03.041 | E4
Gilliland AL. After praise and encouragement: emotional support strategies used by birth doulas in the USA and Canada. Midwifery. 2011;27(4):525–31.20850916 | E7
Gilliland AL. Beyond holding hands: the modern role of the professional doula. J Obstet Gynecol Neonatal Nurs. 2002;762–9. | E4
Giordano J, Surita FG. The role of the respectful maternity care model in Sao Paulo, Brazil: A cross-sectional study. Birth. 2019;46(3):509–516.31435983 | E4
Gjerdingen DK, McGovern P, Pratt R, Johnson L, Crow S. Postpartum doula and peer telephone support for postpartum depression: a pilot randomized controlled trial. Randomized Controlled Trial. Journal of Primary Care & Community Health. 2013;4(1):36–43. | E4
Goldbort J. Postpartum depression: bridging the gap between medicalized birth and social support. Int J Childbirth Educ. 2002;17(4):11–17. | E7
Gorsline-Flamm E. Prenatal, labor and delivery support through doula-interpreters. Int J Childbirth Educ. 2002;17(2):20–21. | E4
Greiner KS, Hersh AR, Hersh SR, . The Cost-Effectiveness of Professional Doula Care for a Woman’s First Two Births: A Decision Analysis Model. J Midwifery Womens Health. 2019;64(4):410–420.31034756 | E6
Greiner KS, Hersh AR, Hersh SR, Gallagher AC, Caughey AB, Tilden EL. Cost-Effectiveness of Continuous Support From a Layperson During a Woman’s First Two Births. Review. J Obstet Gynecol Neonatal Nurs. 2019;48(5):538–551. | E4
Hall WA, Tomkinson J, Klein MC. Canadian care providers’ and pregnant women’s approaches to managing birth: minimizing risk while maximizing integrity. Qualitative Health Research. 2012;22(5):575–86.21940939 | E4
Hardy Baker S. Military Doulas: The Doula Dialogue. Midwifery Today. 2018;(127):34–34. | E7
Harris SJ, Janssen PA, Saxell L, Carty EA, MacRae GS, Petersen KL. Effect of a collaborative interdisciplinary maternity care program on perinatal outcomes. CMAJ Canadian Medical Association Journal. 2012;184(17):1885–92.22966055 | E2
Harte JD, Sheehan A, Stewart S, Foureur M. The Birth Unit Design’s influence on women’s birth supporters. Women & Birth. 2013;26:S28–9. doi:10.1016/j.wombi.2013.08.182 | E7
Harte JD, Sheehan A, Stewart SC, Foureur M. Childbirth Supporters’ Experiences in a Built Hospital Birth Environment: Exploring Inhibiting and Facilitating Factors in Negotiating the Supporter Role. HERD: Health Environments Research & Design Journal. 2016;9(3):135–61.26794236 | E7
Haugaard A, Tvedte SL, Severinsen MS, Henriksen L. Norwegian multicultural doulas’ experiences of supporting newly-arrived migrant women during pregnancy and childbirth: A qualitative study. Sexual & reproductive healthcare: official journal of the Swedish Association of Midwives. 2020;26:100540.32622149 | E4
Helena L, Amani E, Anna W, Nataliia T, Rhonda S, Erica S. Multi-tasking community-based bilingual doulas are bridging gaps-Despite standing on fragile ground. A qualitative study of doulas’ experiences in Sweden. Midwifery. 2021;105:103231.34979361 | E4
Helwick C. Presence of ‘doulas’ during difficult labors may reduce rate of C-sections. Medical Tribune. 1998;39(12):16–16. | E7
Hilton L. Doulas on duty. Nursing Spectrum -- New York & New Jersey Edition. 2007;19A(17):31–31. | E7
Himes B. Medicaid, Doulas and Reducing Maternal and Infant Mortality Rates in the United States. Neonatology Today. 2021;16(12):56–57. | E4
Hodnett ED, Downe S, Walsh D. Alternative versus conventional institutional settings for birth [Systematic Review]. Cochrane Database Syst Rev. 2012. p. 8. | E4
Holder K. Birthing support and breastfeeding initiation in Somaliland: experiences at the Edna Adan Maternity Hospital in Hargeisa, Somaliland. East African Journal of Public Health. 2011;8(1):38–41.22066281 | E4
Hongyu Z, Mei C. Bridging the Gap between Home and Hospital: Pre-labor Doula Service in Hayi Mom Maternity Home. Midwifery Today. 2019;(132):43–43. | E4
Horner J. Correction:…Silverwood-Cope O. Going underground… Kemi Johnson and Joy Horner. Association of Radical Midwives Autumn. 2021: 170; 24-28. Midwifery Matters: Association of Radical Midwives; 2021. p. 3–3. | E7
Horstman HK, Anderson J, Kuehl RA. Communicatively Making Sense of Doulas within the U.S. Master Birth Narrative: Doulas as Liminal Characters. Health Communication. 2016;32(12):1510–1519.27813661 | E4
Hotelling B, Amis D, Green J. Care Practices that Promote Normal Birth #3: Continuous Labor Support. J Perinatal Educ. 2004;13(2):16–19. | E7
Howe C, Doser L, Guise J, Emeis C, Jacobsen-Dunlop N, C OH. Doula care for vulnerable populations. Communicating Nursing Research. 2010;43:287–287. | E6
Hulsbergen M, van der Kwaak A. The influence of quality and respectful care on the uptake of skilled birth attendance in Tanzania. BMC Pregnancy Childbirth. 2020;20(1). doi:10.1186/s12884-020-03278-z | E4
Humphreys A. Prenatal Maternal Stress: Neurological and Physiological Impacts on Offspring. Journal of Prenatal & Perinatal Psychology & Health. Lancaster, California: Association for Prenatal & Perinatal Psychology & Health; 2015. p. 17–27. | E7
Humphries ML, Korfmacher J. The good, the bad, and the ambivalent: Quality of alliance in a support program for young mothers. Infant Mental Health Journal. 2012;33(1):22–33.28520111 | E4
Hunie Asratie M, Mohammed Assfaw H, Abuhay M. Labor Companionship in Labor and Delivery at Debremarkos Town Public Health Facilities: Magnitude and Associated Factors. International Journal of Women’s Health. 2021;13:815–827. | E4
Hunter C. Intimate space within institutionalized birth: women’s experiences birthing with doulas. Anthropology & Medicine. 2012;19(3):315–26.22870904 | E4
ICEA. ICEA position paper: the role and scope of the doula. Int J Childbirth Educ. 1999;14(1):38–45. | E7
ICEA. Newly certified ICEA childbirth educators (ICCEs), doulas (ICDs), postnatal educators (ICPEs), and perinatal fitness educators (ICPFEs). Int J Childbirth Educ. Raleigh, North Carolina: International Childbirth Education Association; 2005. p. 33–33. | E7
ICEA. Newly Certified ICEA Childbirth Educators (ICCEs), Postnatal Educators (ICPEs), Perinatal Fitness Educators (ICPFEs), and Doulas (ICDs). Int J Childbirth Educ. Raleigh, North Carolina: International Childbirth Education Association; 2008. p. 40–40. | E7
IJCE. Correction…March 2008 … Why women still need a doula when using a midwife. Int J Childbirth Educ. Raleigh, North Carolina: International Childbirth Education Association; 2008. p. 36–36. | E7
Iobst SE, Phillips AK, Wilson C. Shared Decision-Making During Labor and Birth Among Low-Risk, Active Duty Women in the U.S. Military. Military Medicine. 2021;26:26. | E4
Ireland S, Montgomery-Andersen R, Geraghty S. Indigenous Doulas: A literature review exploring their role and practice in western maternity care. Review. Midwifery. 2019;75:52–58.31003022 | E6
Jackson K. Nurturing the Family: A Doulas Guide to Supporting New Parents, 2nd Edition, by Jacqueline Kelleher. Clinical Lactation. 2020;11(4):212–212. doi:10.1891/Article_12_Nurturing_the_family_book_review_BR | E7
Jacobson A. Reducing Disparities in Maternal Mortality. Neonatology Today. 2020;15(2):22–23. | E7
Johansson M, Fenwick J, Premberg A. A meta-synthesis of fathers’ experiences of their partner’s labour and the birth of their baby. Midwifery. 2015;31(1):9–18.24906562 | E4
Jones L, Othman M, Dowswell T, . Pain management for women in labour: an overview of systematic reviews [Systematic Review]. Cochrane Database Syst Rev. 2013. p. 6. | E7
Jordan ET, Van Zandt SE, Oseroff M. Educating undergraduate nursing students as birth companions. Nursing & Health Care Perspectives. 2001;22(2):89–91. | E4
Jumah NA, Tyler L, Turuba R, . On the path to reclaiming Indigenous midwifery: Co-creating the Maternal Infant Support Worker pilot program. Int J Gynaecol Obstet. 2021;155(2):203–210.34491574 | E7
Kalau M. The Birth of the European Doula Network. Midwifery Today. 2018;(126):36–37. | E4
Kane A. The benefits of doula service in the high-risk pregnancy. Int J Childbirth Educ. 1997;12(3):18–19. | E7
Kane Low L, Moffat A, Brennan P. Doulas as community health workers: lessons learned from a volunteer program. J Perinatal Educ. 2006;15(3):25–33. | E4
Kang HK. Influence of culture and community perceptions on birth and perinatal care of immigrant women: doulas’ perspective. J Perinatal Educ. 2014;23(1):25–32. | E6
Kathawa CA, Arora KS, Zielinski R, Low LK. Perspectives of Doulas of Color on their Role in Alleviating Racial Disparities in Birth Outcomes: A Qualitative Study. J Midwifery Womens Health. 2021;26:26. | E7
Kayne MA, Greulich MB, Albers LL. Doulas: an alternative yet complementary addition to care during childbirth. Review. Clinical Obstetrics & Gynecology. 2001;44(4):692–703.11600852 | E6
Keenan P. Benefits of massage therapy and use of a doula during labor and childbirth. Review. Alternative Therapies in Health & Medicine. 2000;6(1):66–74.10631824 | E6
Kehoe SL, Bathgate SL, Macri CJ. Use of a doula for labor coaching in a patient with indolent systemic mastocytosis in pregnancy. Case Reports. Obstetrics & Gynecology. 2006;107(2 Pt 2):514–6.16449169 | E10
Kendall-Tackett K. Childbirth-Related Posttraumatic Stress Disorder and Breastfeeding: Challenges Mothers Face and How Birth Professionals Can Support Them. Journal of Prenatal & Perinatal Psychology & Health. 2015;29(4):264–275. | E7
Kirkham M. DOULAS AND INTIMATE LABOUR. Midwifery Matters. 2018;(157):21–21. | E2
Klein M. The Jewish midwife. Midwifery Today. 2001;(60):54–66. | E4
Klein MC. Guest Editorial. Many Women and Providers Are Unprepared for an Evidence-Based, Educated Conversation About Birth. J Perinatal Educ 2011;20(4):185–187. doi:10.1891/1058-1243.20.4.185 | E9
Knape N, Schnepp W, Krahl A, Zu Sayn-Wittgenstein F. [The efficiency of one-to-one support during labour - a literature analysis]. Zeitschrift fur Geburtshilfe und Neonatologie. 2013;217(5):161–72.24170441 | E7
Kobayashi S, Hanada N, Matsuzaki M, . Assessment and support during early labour for improving birth outcomes [Systematic Review]. Systematic Review. Cochrane Database Syst Rev. 2017;8:8. | E4
Kolb K. The Other Side of Doula Work. Midwifery Today. Summer2018 2018;(126):35–35. | E4
Kozhimannil KB, Attanasio LB, Hardeman RR, O’Brien M. Doula care supports near-universal breastfeeding initiation among diverse, low-income women. Research Support, N.I.H., Extramural. J Midwifery Womens Health. 2013;58(4):378–82.23837663 | E4
Kozhimannil KB, Hardeman RR, Alarid-Escudero F, Vogelsang CA, Blauer-Peterson C, Howell EA. Modeling the Cost-Effectiveness of Doula Care Associated with Reductions in Preterm Birth and Cesarean Delivery. Research Support, N.I.H., Extramural. Birth. 2016;43(1):20–7.26762249 | E6
Kozhimannil KB, Vogelsang CA, Hardeman RR, Prasad S. Disrupting the Pathways of Social Determinants of Health: Doula Support during Pregnancy and Childbirth. Journal of the American Board of Family Medicine: JABFM. 2016;29(3):308–17.27170788 | E4
Krapf J. Revitalizing Midwifery: Reimagining the Doula’s Role. Midwifery Today. 2019;(130):51–55. | E4
Kuczkowski KM. Doctors and doulas in the labor and delivery suite. Letter. Acta Anaesthesiologica Scandinavica. 2007;51(7):954–5. | E7
Kuczkowski KM. Female companionship during labor: a crucial resource in times of stress…Pascali-Bonaro D, Kroeger M. Continuous female companionship during childbirth: a crucial resource in times of stress or calm. J Midwifery Womens Health. 2004;49(Suppl 1):19-27. J Midwifery Womens Health. 2004;49(6):552–552. doi:10.1016/j.jmwh.2004.08.004 15544988 | E7
Lagendyk LE, Thurston WE. A case study of volunteers providing labour and childbirth support in hospitals in Canada. Midwifery. 2005;21(1):14–22. doi:10.1016/j.midw.2004.07.002 15740813 | E4
LaMancuso K, Goldman RE, Nothnagle M. “Can I Ask That?”: Perspectives on Perinatal Care After Resettlement Among Karen Refugee Women, Medical Providers, and Community-Based Doulas. J Immigrant Minority Health. 2016;18(2):428–35. | E4
Lanning R. Doulas and Nurses Partner to Support Skin-to-Skin Care in the Operating Room…2019 AWHONN Convention, June 8-12, 2019, Atlanta, Georgia. J Obstet Gynecol Neonatal Nurs. 2019;48:S45–S45. doi:10.1016/j.jogn.2019.04.077 | E4
Lanning RK, Klaman SL. Evaluation of an Innovative, Hospital-Based Volunteer Doula Program. J Obstet Gynecol Neonatal Nurs. 2019;48(6):654–663. | E7
Lantz PM, Low LK, Varkey S, Watson RL. Doulas as childbirth paraprofessionals: results from a national survey. Womens Health Issues. 2005;15(3):109–16.15894196 | E4
Lantz PM, Low LK, Watson RL. Doulas’ views on the rewards and challenges of their work. Int J Childbirth Educ. 2004;19(4):31–34. | E4
Lassi ZS, Bhutta ZA. Community-based intervention packages for reducing maternal and neonatal morbidity and mortality and improving neonatal outcomes [Systematic Review]. Systematic Review. Cochrane Database Syst Rev. 2015;3:3. | E6
Leao MR, Bastos MA. ["Doulas" supporting women during labor: the experience at the Sofia Feldeman Hospital]. Review. Revista Latino-Americana de Enfermagem. 2001;9(3):90–4.12040796 | E9
Lee Phillips D, Kelly C. Social Work Should Embrace Doulas. Health & Social Work. 2014;39(2):117–120.24946428 | E4
Leslie MS, Storton S. Step 1: offers all birthing mothers unrestricted access to birth companions, labor support, professional midwifery care: the coalition for improving maternity services. J Perinatal Educ. 2007;16 Suppl 1:10S–9S. | E7
Lewis JA. [Commentary on] A randomized control trial of continuous support in labor by a lay doula. AmJ Maternal Child Nurs. 2007;32(1):62–62. doi:10.1097/00005721-200701000-00020 | E7
Lieberman AB. Do you need a doula? American Baby. 1993;55(1):54–58. | E7
Lieser MA. Birth Behind Bars: The Difference Trauma-informed Doula Care Can Make. Midwifery Today. 2019;(130):34–36. | E7
Lieser MA. DONA’s youngest certified doula. Midwifery Today with International Midwife. 2012. p. 38, 66–7. | E4
Lim IR. Baby Is Listening. Midwifery Today. 2019;(129):32–35. | E4
Lindner SL, McGrath JM. Family-Centered Care and Continuous Labor Support. Newborn & Infant Nursing Reviews. 2012;12(2):70–72. doi:10.1053/j.nainr.2012.03.004 | E4
Lindow SW, Hendricks MS, Thompson JW, van der Spuy ZM. The effect of emotional support on maternal oxytocin levels in labouring women. Clinical Trial Randomized Controlled Trial. European Journal of Obstetrics, Gynecology, & Reproductive Biology. 1998;79(2):127–9.9720828 | E4
Lucas L, Wright E. Attitudes of Physicians, Midwives, and Nurses About Doulas: A Scoping Review. Review. MCN Am J Matern Child Nurs. 2019;44(1):33–39.30531588 | E7
Lundgren I. Swedish women’s experiences of doula support during childbirth. Midwifery. 2010;26(2):173–80.18639959 | E4
Lusher B. Doula Care for Refugee Families. Midwifery Today. Spring2018 2018;(125):52–53. | E1
MacTavish J. Supporting LGBTQ Families: A Brief Cultural Competency Guide for Childbirth Educators and Doulas. Int J Childbirth Educ. 2011;26(3):7–10. | E6
Mafetoni RR, Kakuda Shimo AK. NON-PHARMACOLOGICAL METHODS FOR PAIN RELIEF DURING LABOR: INTEGRATIVE REVIEW. Revista Mineira de Enfermagem. 2014;18(2):513–520. doi:10.5935/1415-2762.20140037 | E6
Mains H. An intimate dance with birthing women. Midwifery Today. Spring2004 2004;(69):21–23. | E7
Mallak J. Focal point on labor support. Second stage considerations for doulas. Int J Childbirth Educ. Spring99 1999;14(1):6–7. | E4
Mallak J. Why women still need a doula when using a midwife [corrected] [published erratum appears in INT J CHILDBIRTH EDUC 2008 Sep;23(3):36]. Int J Childbirth Educ. 2008;23(1):8–9. | E4
Mallak JS. A year to remember. Int J Childbirth Educ. 2007;22(3):33–34. | E7
Mallak JS. Fathers and labor support. Int J Childbirth Educ. 2002;17(2):16–17. | E4
Mallak JS. Focal point on labor support: how a birth doula affects breastfeeding. Int J Childbirth Educ. 1999;14(2):10–10. | E4
Mallak JS. ‘Risk management’ considerations for childbirth educators and birth doulas. Int J Childbirth Educ. 1998;13(1):6–7. | E4
Mallak JS. Why be a postpartum doula? (When I don’t even want to clean my own house!). Int J Childbirth Educ. 2005;20(1):31–32. | E4
Manning-Orenstein G. A birth intervention: the therapeutic effects of Doula support versus Lamaze preparation on first-time mothers’ working models of caregiving. Altern Ther Health Med. 1998;4(4):73–81.9656503 | E4
Marrero L, Odaléa Maria B. Institutional violence during the parturition process in Brazil: integrative review. Revista Brasileira de Enfermagem. 2018. p. 1152–1161.29924146 | E7
Marsden S. A doula’s place is in the maternity theatre. Midwifery Matters. 2020;(164):18–19. | E7
Marshall D. Birth Companions: working with women in prison giving birth. Br J Midwifery. 2010;18(4):225–228. doi:10.12968/bjom.2010.18.4.47372 | E4
Mather N. Postnatal doulas: nurturing the family. AIMS Journal. 2019;31(2):28–31. | E7
Mayes JH, Mahoney JA. Daisy C.H.A.I.N. Creating Healthy Alliances In New-Mothering. Midwifery Today. 2013;(106):58–59.23847902 | E6
McComish JF, Campell-Voytal K, Rowland C. Postpartum doula care: content and process. R. 2005:1p–1p. | E7
McComish JF, Visger JM. Domains of postpartum doula care and maternal responsiveness and competence. J Obstet Gynecol Neonatal Nurs 2009;38(2):148–56. | E7
McGarry A, Stenfert Kroese B, Cox R. How Do Women with an Intellectual Disability Experience the Support of a Doula During Their Pregnancy, Childbirth and After the Birth of Their Child? J Applied Res Intellectual Disab. 2016;29(1):21–33. | E4
McIntyre MM. When the birth companions were born. Johns Hopkins Nurs. 2009;7(3):4–4. | E7
McKellar L. Partnership for change: Skilled birth attendants and traditional birth attendants working together. Women Birth. 2011;24:S33–S33. doi:10.1016/j.wombi.2011.07.107 | E7
McLeish J, Redshaw M. “Being the best person that they can be and the best mum”: a qualitative study of community volunteer doula support for disadvantaged mothers before and after birth in England. BMC Pregnancy Childbirth. 2019;19(1):21.30630445 | E4
McLeish J, Redshaw M. A qualitative study of volunteer doulas working alongside midwives at births in England: Mothers’ and doulas’ experiences. Midwifery. 2018;56:53–60.29078074 | E4
McMahon M, Morris M. DOULAS AND MIDWIVES: A POWERFUL ALLIANCE. Practising Midwife. 2018;21(3):09–13. | E7
McMillan J. Childbirth and the Canadian military family… volunteer pregnancy and labour companion program. Nursing BC. 1997;29(3):22–24. | E7
Meadow SL. Defining the doula’s role: fostering relational autonomy. Health Expectations. 2015;18(6):3057–68.25327532 | E4
Melchiors H. Doulas and Intimate Labour: Boundaries, Bodies, and Birth. Med Anthro Qrtly. 2017;31(1). doi:10.1111/maq.12325 | E7
Meyer BA, Arnold JA, Pascali-Bonaro D. Social support by doulas during labor and the early postpartum period. Hosp Physician. 2001;37(9):57–65. | E7
Meyer H, Kirwan A, Dealy K. Expanding the doula model: an Illinois replication story. Zero to Three. 2005;25(5):35–42. | E7
Middleton W. Postpartum doulas: vital members of the maternity care team. Int J Childbirth Educ. 2003;18(2):8–10. | E7
Moore S. Is the doula an intervention? Int J Childbirth Educ. 2004;19(4):22–23. | E7
Moray S, Lindberg J, Stein I, Thornton S, Beauregard M, Schwartz B. Question of the quarter…the birth community. Midwifery Today. 2000;(56):8–67. | E7
Morgan C. Mama Doula. Int J Childbirth Educ. 2006;21(2):13–14. | E7
Morhason-Bello IO, Adedokun BO, Ojengbede OA. Social support during childbirth as a catalyst for early breastfeeding initiation for first-time Nigerian mothers. Int Breastfeeding J. 2009;4:7p–7p. doi:10.1186/1746-4358-4-16 | E4
Morton CH, Henley MM, Seacrist M, Roth LM. Bearing witness: United States and Canadian maternity support workers’ observations of disrespectful care in childbirth. Birth. 2018;45(3):263–274.30058157 | E4
Morton CH, Simkin P. Can respectful maternity care save and improve lives? Birth: Issues in Perinatal Care. 2019: 391–395. | E4
Mosley EA, Lanning RK. Evidence and guidelines for trauma-informed doula care. Review. Midwifery. 2020;83:102643.32014617 | E2
Mosley EA, Pratt M, Besera G, . Evaluating Birth Outcomes From a Community-Based Pregnancy Support Program for Refugee Women in Georgia. Frontiers in Global Womens Health. 2021;2:655409. | E7
Mottl-Santiago J, Herr K, Rodrigues D, Walker C, Walker C, Feinberg E. The Birth Sisters Program: A Model of Hospital-Based Doula Support to Promote Health Equity. Historical Article. J Health Care Poor Underserved. 2020;31(1):43–55. | E7
Munabi-Babigumira S, Glenton C, Lewin S, Fretheim A, Nabudere H. Factors that influence the provision of intrapartum and postnatal care by skilled birth attendants in low- and middle-income countries: a qualitative evidence synthesis. Cochrane Database Syst Rev. 2018;2:2. | E6
National Partnership for Women & Families. Continuous Support for Women During Childbirth: 2017 Cochrane Review Update Key Takeaways. J Perinatal Educ. 2018;27(4):193–197. doi:10.1891/1058-1243.27.4.193 | E7
Neel K, Goldman R, Marte D, Bello G, Nothnagle MB. Hospital-based maternity care practitioners’ perceptions of doulas. Birth. 2019;46(2):355–361.30734958 | E4
NewsRX, LLC. U of M Researchers Find that Doula Care for Low-Income Women Could Save Taxpayers Money. NewsRX Science. March 10, 2013. | E7
Newton P. Continuing education: earning contact hours. The doula’s role during L&D. Healthcare Traveler. 2005;12(10):57–59. | E7
Nguyen TC, Donovan EE, Wright ML. Doula Support Challenges and Coping Strategies during the COVID-19 Pandemic: Implications for Maternal Health Inequities. Health Communication. 2021:1–7. | E4
Nichols J. Media Reviews. Doulas and Intimate Labor: Boundaries, Bodies, and Birth. Midwifery Today. Spring2018 2018;(125):62–62. | E7
Nichols TR, Love H. Providing Reproductive Health Promotion in Drug Treatment Clinics: A Formative Evaluation of a Pilot Program. Calif J Health Promo. 2019;17(2):51–61. doi:10.32398/cjhp.v17i2.2289 | E4
Nolan M. Supporting women in labour: the doula’s role. Modern Midwife. 1995;5(3):12–5. | E7
Nutrition Health Review. Birth coaching makes little difference. Nutrition Health Rev: The Consumer’s Medical Journal. 2006;(94):18–18. | E4
Olson D. ICEA certification update. ICEA to offer Doula certification. Int J Childbirth Educ.1996;11(4):7–7. | E7
Ooijens JC, Bakker JJH, de Graaf IM. Hospital-based Birth Support for Women with Trauma: A Pilot Study of a Clinical Doula Program in the Netherlands. Journal of Prenatal & Perinatal Psychology & Health. 2018;32(3):242–249. | E4
Oparah JC, James JE, Barnett D, . Creativity, Resilience and Resistance: Black Birthworkers’ Responses to the COVID-19 Pandemic. Frontiers in Sociology. 2021;6:636029.33869584 | E4
Parkinson D. Birth companions. Midwifery Matters. 2005;(107):41–41. | E7
Pascali-Bonaro D, Arnold J. Nurturing beginnings; postpartum doula care -- past, present and future. In: R. New Zealand College of Midwives; 2012:34–34. | E10
Pascali-Bonaro D, Kroeger M. Continuous female companionship during childbirth: a crucial resource in times of stress or calm. Review. J Midwifery Womens Health. 2004;49(4 Suppl 1):19–27.15236700 | E7
Pascoe JM. Social support during labor and duration of labor: a community-based study. Pub Health Nurs.1993. p. 97–9.8378240 | E3
Paterno MT, Van Zandt SE, Murphy J, Jordan ET. Evaluation of a student-nurse doula program: an analysis of doula interventions and their impact on labor analgesia and cesarean birth. J Midwifery Women’s Health. 2012;57(1):28–34.22251909 | E3
Patz A. Relieving labor pain. American Baby. 2002;64(8):63–67. | E10
Paynter M, Matheson L, McVicar L, . Peer doula support training for Black and Indigenous groups in Nova Scotia, Canada: A community-based qualitative study. Public Health Nursing. 2021;11:11. | E4
Pengelly H. Doula-ing from a distance: better than nothing. AIMS Journal. 2020;32(2):35–36. | E2
Perez P. Nurturing laboring women through the years. Int J Childbirth Educ. 2009;24(4):19–21. | E7
Perez PG, Herrick LM. Doulas: exploring their roles with parents, hospitals, & nurses. AWHONN Lifelines. 1998;2(2):54–5.9633309 | E7
Pincus J. Media reviews. The birth partner: a complete guide to childbirth for dads, doulas, and all other labor companions, third edition. Birth: Issues in Perinatal Care. 2009;36(1):91–92. doi:10.1111/j.1523-536x.2008.304_2.x | E7
Portela A, Qazi SA, Tran N. Implementation research for maternal, newborn and child health. Acta Paediatrica. 2018;107(471):3–6. doi:10.1111/apa.14641 | E7
Porter K. The Black Parent Initiative’s Sacred Roots Community-based Doula Program. Midwifery Today. Winter2017 2017;(124):36–37.29912533 | E4
Potvin LA, Doula B, Brown HK, Cobigo V. Social support received by women with intellectual and developmental disabilities during pregnancy and childbirth: An exploratory qualitative study. Midwifery. 2016;37:57–64. doi:10.1016/j.midw.2016.04.005 27217238 | E4
Power C, Williams C, Brown A. Does childbirth experience affect infant behaviour? Exploring the perceptions of maternity care providers. Midwifery. 2019;78:131–139. doi:10.1016/j.midw.2019.07.021 31437757 | E4
Punger D. Importance of continuous doula support during labor. Comment Letter. American Family Physician. 2004;70(3):448.15317433 | E7
Pyone T, Adaji S, Madaj B, Woldetsadik T, van den Broek N. Changing the role of the traditional birth attendant in Somaliland. Int J Gynaecol Obstet. 2014;127(1):41–6.24938771 | E4
Raphael D. New patterns in Doula client relations. Midwife, Health Visitor & Community Nurse. 1988;24(9):376–9. | E7
RCM. Can doulas provide a continuity of care that midwives are unable to? RCM Midwives. 2007;10(10):490.18041324 | E7
RCM. Doulas: position statement. Royal College of Midwives: Redactive Publishing Ltd.; 2004. p. Page: 1–Page: 1. | E7
Reime B, Klein MC, Kelly A, . Do maternity care provider groups have different attitudes towards birth? BJOG 2004;111(12):1388–93.15663124 | E4
Render-Graham E. Holding Space for Birthworkers. Midwifery Today. 2019;(130):43–43. | E7
Richards E, Lanning RK. Volunteer doulas’ experiences supporting cesarean births: A qualitative analysis for preliminary program evaluation. Midwifery. 2019;77:117–122.31319366 | E7
Richards MPM. Doulas and the quality of maternity services. Birth: Issues in Perinatal Care. 1992;19(1):40–41. | E7
Richardson RNM. Doulas Supporting Military Overseas. Midwifery Today. 2018;(127):35–35. | E7
Robinson J. Birth companions and postnatal depression. AIMS Journal. 1999;11(1):16–16. | E7
Romano A. Research Summaries for Normal Birth. J Perinatal Educ. Summer2005 2005;14(3):56–60. doi:10.1624/105812405X57606 | E7
Rosen P. Mother’s little helper. American Baby. Des Moines, Iowa: Meredith Corporation; 2002. p. 32–37. | E10
Rosen P. Supporting women in labor: analysis of different types of caregivers. J Midwifery Womens Health. 2004;49(1):24–31. doi:10.1016/j.jmwh.2003.10.013 14710137 | E6
Ross LE, Steele LS, Epstein R. Service use and gaps in services for lesbian and bisexual women during donor insemination, pregnancy, and the postpartum period. Journal of Obstetrics & Gynaecology Canada: JOGC. 2006;28(6):505–511.16857118 | E4
Ross M. Novel Doula Training for Incarcerated Women and Those at Risk Expands and Grows. Science of Caring. 2016:2–1. | E7
Ross M. UCSF Students and Faculty Offer Doula Services to Transform Lives of Incarcerated Women. Science of Caring. 2014:7–7. | E10
Roth LM, Henley MM, Seacrist MJ, Morton CH. North American Nurses’ and Doulas’ Views of Each Other. J Obstet Gynecol Neonatal Nurs. 2016;45(6):790–800. | E4
Rouse DJ. [Commentary on] A randomized controlled trial of continuous labor support for middle-class couples: effect on cesarean delivery rates. Obstetrical & Gynecological Survey. 2008;63(10):620–621. | E10
Safarzadeh A, Shafipour V, Salar A. Expectant Mothers’ Experiences with Lay Doulas in Maternity Units of Hospitals in Impoverished Areas of Iran: A Qualitative Study. Iranian Journal of Nursing and Midwifery Research. 2018;23(6):437–443.30386393 | E4
Sager S, Sippert G. Focal point on labor support and postnatal education. Birth/parent companions make a difference. Int J Childbirth Educ. 2000;15(2):14–16. | E7
Saha S, Varghese B. Cost-effectiveness of the Yashoda Programme. Journal of Health Management. 2017;19(2):255–263. doi:10.1177/0972063417699688 | E4
Salehi A, Fahami F, Beigi M. The effect of presence of trained husbands beside their wives during childbirth on women’s anxiety. Iranian Journal of Nursing and Midwifery Research. 2016;21(6):611–615.28194202 | E4
Salomonsson B, Wijma K, Alehagen S. Swedish midwives’ perceptions of fear of childbirth. Midwifery. 2010;26(3):327–337. doi:10.1016/j.midw.2008.07.003 18774630 | E4
Salt KN. Doula dilemmas. Int J Childbirth Educ. 2002;17(3):18–20. | E7
Sarah Beake R, Associate R, Chang Y-S, . Experiences of early labour management from perspectives of women, labour companions and health professionals: A systematic review of qualitative evidence. Midwifery. 2018;57:69–84.29223042 | E6
Sauls DJ. Effects of labor support on mothers, babies, and birth outcomes. Review. J Obstet Gynecol Neonatal Nurs. 2002;31(6):733–41. | E6
Schroeder C, Bell J. Doula birth support for incarcerated pregnant women. Public Health Nursing. 2005;22(1):53–8.15670325 | E4
Schroeder CA, Bell JF. Hard time: nursing and incarcerated populations: labor support for incarcerated pregnant women: the Doula Project…34th Annual Communicating Nursing Research Conference/15th Annual WIN Assembly, ‘Health Care Challenges Beyond 2001: Mapping the Journey for Research and Practice,’ held April 19-21, 2001 in Seattle, Washington. Communicating Nursing Research. 2001 Spring 2001;34:127–127. | E7
Schuster JM. Wholistic health. Doulas help women take control of childbirth. Journal of Clinical Systems Management. 2003;5(2):7–18. | E7
Schwartz J. Enhancing the birth experience: the doula as part of the hospital maternity program. Int J Childbirth Educ. 2002;17(1):18–19. | E7
Schytt E, Wahlberg A, Eltayb A, Small R, Tsekhmestruk N, Lindgren H. Community-based doula support for migrant women during labour and birth: study protocol for a randomised controlled trial in Stockholm, Sweden (NCT03461640). BMJ Open. 2020;10(2):e031290. | E4
Schytt E, Wahlberg A, Small R, Eltayb A, Lindgren H. The community-based bilingual doula - A new actor filling gaps in labour care for migrant women. Findings from a qualitative study of midwives’ and obstetricians’ experiences. Sexual & reproductive healthcare: official journal of the Swedish Association of Midwives. 2021;28:100614.33813256 | E7
Scott KD, Berkowitz G, Klaus M. A comparison of intermittent and continuous support during labor: a meta-analysis. American Journal of Obstetrics & Gynecology 1999. p. 1054–9.10329855 | E6
Scott KD, Klaus PH, Klaus MH. The obstetrical and postpartum benefits of continuous support during childbirth. Review. Journal of Womens Health & Gender-Based Medicine. 1999;8(10):1257–64. | E8
Searcy JJ, Castaneda AN. On the Outside Looking In: A Global Doula Response to COVID-19. Frontiers in Sociology. 2021;6:613978.33869566 | E4
Shalev J. Having a doula during labor and delivery. Letter. Midwifery Today & Childbirth Education. 1992;(24):8–9. | E10
Shlafer RJ, Hellerstedt WL, Secor-Turner M, Gerrity E, Baker R. Doulas’ Perspectives about Providing Support to Incarcerated Women: A Feasibility Study. Public Health Nursing. 2015;32(4):316–26.24980835 | E4
Silva RM, Barros NF, Jorge HM, Melo LP, Ferreira Junior AR. [Qualitative evidence of monitoring by doulas during labor and childbirth]. Review. Ciencia & Saude Coletiva. 2012;17(10):2783–94.23099764 | E9
Simkin P, Hull K. Pain, Suffering, and Trauma in Labor and Prevention of Subsequent Posttraumatic Stress Disorder. J Perinatal Educ. New York, New York: Springer Publishing Company, Inc.; 2011. p. 166–176. | E7
Simkin P. Doulas: nurturing and protecting women’s memories of their birth experiences. Int J Childbirth Educ. 2004;19(4):16–19. | E7
Simkin P. Emotional support for the woman with an epidural. Int J Childbirth Educ. 2003;18(3):4–7. | E7
Simkin PP, O’Hara M, Simkin PP, O’Hara M. Nonpharmacologic relief of pain during labor: systematic reviews of five methods. American Journal of Obstetrics & Gynecology. 2002;186(5):S131–59. doi:10.1067/mob.2002.122382 12011879 | E6
Simon RM, Johnson KM, Liddell J. Amount, Source, and Quality of Support as Predictors of Women’s Birth Evaluations. Birth. 2016;43(3):226–32.26991407 | E4
Sippert G. Focal point on labor support. Attachment and bonding: the Doula’s role. Int J Childbirth Educ. 1998;13(4):26–27. | E7
Smid M, Campero L, Cragin L, Gonzalez Hernandez D, Walker D. Bringing two worlds together: exploring the integration of traditional midwives as doulas in Mexican public hospitals. Health Care for Women International. 2010;31(6):475–98.20461600 | E4
Smith CK. Media reviews. Being born: the doula’s role. Midwifery Today. 2009;(90):59–59. | E7
Sosa R, Kennell J, Klaus M, Robertson S, Urrutia J. The effect of a supportive companion on perinatal problems, length of labor, and mother-infant interaction. Clinical Trial Randomized Controlled Trial Research Support, U.S. Gov’t, P.H.S. New England Journal of Medicine. 1980;303(11):597–600. | E4
Sperlich M, Gabriel C, St Vil NM. Preference, knowledge and utilization of midwives, childbirth education classes and doulas among U.S. black and white women: implications for pregnancy and childbirth outcomes. Research Support, N.I.H., Extramural. Social Work in Health Care. 2019;58(10):988–1001.31682786 | E4
Stark MA, Jones M. Advanced Preparation and Positive Labor Support Create an Optimal Experience for Normal Birth. J Perinatal Educ. 2006;15(2):4–7. doi:10.1624/105812406X107753 | E7
Steel A, Adair R. The ghost in the room: the role of doulas in maternity care in Australia. Women & Birth. 2011;24:S44–S44doi10.1016/j.wombi.2011.07.141 | E4
Steel A, Diezel H, Frawley J, Wardle J, Adams J. Providing maternity care from outside the system: perspectives of complementary medicine practitioners. Journal of Interprofessional Care. 2020:1–9. | E7
Stein MT, Kennell JH, Fulcher A. Benefits of a doula present at the birth of a child. Case Reports. Journal of Developmental & Behavioral Pediatrics. 2004;25(5 Suppl):S89–92.15502542 | E7
Stevens J, Dahlen H, Peters K, Jackson D. Midwives’ and doulas’ perspectives of the role of the doula in Australia: a qualitative study. Midwifery. 2011;27(4):509–16.20889246 | E4
Stitt C, Brockman K. Women’s Beliefs Regarding the Importance of Information About Birth Healthcare Provider Options: An Experimental Approach. Int J Childbirth Educ. 2019;34(1):16–22. | E7
Stockton A. Mother’s mouthpiece or clinician’s curse: the doula debate continues. MIDIRS Midwifery Digest: MIDIRS; 2010a. p. 57–58. | E7
Stockton A. NHS doulas’. AIMS Journal. 2012;24(2):16–17. | E7
Stockton A. Prenatal support and preparation for birth--the doula’s role. Practising Midwife. 2010b;13(5):26–7, 30. | E7
Stringer H. For the love of labor -- RNs and doulas working together. NurseWeek California. 2006;19(3):14–16. | E10
Studebaker SS. The birth partner, third edition: a complete guide to childbirth for dads, doulas, and all other labor companions. J Midwifery Womens Health. 2009;54(6):e71–e71. doi:10.1016/j.jmwh.2009.08.010 | E7
Studelska JV. At home in birth. Midwifery Today. Spring2006 2006;(77):32–33. | E7
Suárez-Baquero DFM, Champion JD. Accompanying the Path of Maternity: The Life History of a Colombian Doula. J Perinatal Educ. 2021;30(3):145–158. doi:10.1891/J-PE-D-20-00038 | E4
Summerton JV, Mtileni TR, Moshabela ME. Experiences and perceptions of birth companions supporting women in labour at a District Hospital in Limpopo, South Africa. Curationis. 2021;44(1):e1–e7. | E4
Szarynska M, Kmiec Z, Preis K, Zabul P. The presence of a supporting person during delivery affects cord blood haematopoietic stem cells. Journal of Obstetrics & Gynaecology. 2014;34(3):245–7.24483273 | E10
Tanner T, Lowe NK. Providers speak out! A delphi study of self-competence for childbirth. Communicating Nursing Research. 2012;45:362–362. | E10
Tempfer-Bentz EK, Froese G, Gong Y, . Association of untrained labor companion with operative delivery rate: retrospective study of 2247 women. Journal of Women’s Health. 2011;20(9):1367–71. | E2
Thomassen P, Lundwall M, Wiger E, Wollin L, Uvnas-Moberg K. [Doula--a new concept in obstetrics]. Lakartidningen. 2003;100(51–52):4268–71.14756088 | E7
Thullen MJ, McMillin SE, Korfmacher J, . Father participation in a community-doula home-visiting intervention with young, African American mothers. Infant Mental Health Journal. 2014;35(5):422–34.25798493 | E7
Tiran D. Maternity support therapist programme (birth and postnatal ‘doula’ training). Complementary Therapies in Clinical Practice. 2009;15(2):117–117. doi:10.1016/j.ctcp.2009.02.001 | E7
Torres JM. Breast milk and labour support: lactation consultants’ and doulas’ strategies for navigating the medical context of maternity care. Sociology of Health & Illness. 2013;35(6):924–38.23398567 | E4
Trainor CL. Valuing labor support. A doula’s perspective. AWHONN Lifelines. 2002;6(5):387–9.12420380 | E7
Tritten J, Magri T. From the Editor. The Doula’s Role. Midwifery Today. 2018;(125):5–5. | E7
Tritten J. There’s No Place Like Home. Midwifery Today. 2015;(114):5–5. | E7
Tussey C, Kohlhase A, Davis M, Rigali K, Wolf MJ, Olson C. Integrating Midwives, Doulas, and High-Touch Techniques to Enhance Womens’ Birth Experience…2020 Association of Women’s Health, Obstetric and Neonatal Nurses (AWHONN) Annual Convention, Nov 1-4, 2020. J Obstet Gynecol Neonatal Nurs. 2020;49(6):S48–S49. doi:10.1016/j.jogn.2020.09.083 | E7
Uban NM. Low Income Women’s Expectations, Needs, and Desires for Social Support in the Postpartum Period: A Feasibility Study. University of Minnesota; 2012. | E4
Van Zandt SE, Edwards L, Jordan ET. Lower epidural anesthesia use associated with labor support by student nurse doulas: implications for intrapartal nursing practice. Complementary Therapies in Clinical Practice. 2005;11(3):153–60.16005832 | E4
Van Zandt SE, Kim S, Erickson A. Nursing Student Birth Doulas’ Influence On the Childbearing Outcomes of Vulnerable Populations. J Commun Health Nurs. 2016;33(3):128–38. | E3
Vanderbilt S. Women gathered at birth: the massage birth assistant. Massage & Bodywork. 2000;15(6):24–31. | E4
Varma M. A Doula’s Posit for The Power Of Supportive Touch. Massage & Bodywork. 2020:72–79. | E7
Vaughan M. Doulas. Midwifery Matters. 2002;(95):10–11. | E7
Waisblat V, Langholz B, Bernard FJ, . Impact of a Hypnotically-Based Intervention on Pain and Fear in Women Undergoing Labor. Clinical Trial. International Journal of Clinical & Experimental Hypnosis. 2017;65(1):64–85.27935457 | E2
Waller-Wise R. Fostering Collegial Collaboration Between Labor Nurses and Doulas. Nursing for Women’s Health. 2018;22(3):212–218. | E7
Walsh C. Let’s get personal. Baby steps for better labor. Health (Time Inc Health). 2001;15(8):154–156. | E10
Walsh T, Green J, Shields L. Support in labour: a review of the literature. Birth Issues. 2007;15(3–4):89–97. | E6
Wen X, Korfmacher J, Hans SL. Change over time in young mothers’ engagement with a community-based doula home visiting program. Children & Youth Services Review. 2016;69:116–126. doi:10.1016/j.childyouth.2016.07.023 | E4
Wikberg AM, Bondas TE. Lay Voluntary Doula Caring for the Childbearing Woman and Her Partner. International Journal for Human Caring. 2021;25(1):60–73. doi:10.20467/HumanCaring-D-20-00019 | E4
Wint K, Elias TI, Mendez G, Mendez DD, Gary-Webb TL. Experiences of Community Doulas Working with Low-Income, African American Mothers. Health Equity. 2019;3(1):109–116.31289769 | E4
Wolman WL, Chalmers B, Hofmeyr GJ, Nikodem VC. Postpartum depression and companionship in the clinical birth environment: a randomized, controlled study. American Journal of Obstetrics & Gynecology. 1993;168(5):1388–9 8498417 | E4
Worley E. Gentle birth companions - doulas serving humanity. Midwives. 2011;14(7):44–44. | E7
Yogev S. Support in labour: a literature review. MIDIRS Midwifery Digest. 2004;14(4):486–492. | E6
Yuenyong S, Jirapaet V, O’Brien BA. Support from a close female relative in labour: the ideal maternity nursing intervention in Thailand. Review. Journal of the Medical Association of Thailand. 2008;91(2):253–60.18389993 | E7
Zak R. A Doula’s Journey: Into the World of Birth. Int J Childbirth Educ. 2015;30(4):46–46. | E7
Zhang J, Bernasko JW, Leybovich E, Fahs M, Hatch MC. Continuous labor support from labor attendant for primiparous women: a meta-analysis. Meta-Analysis. Obstetrics & Gynecology. 1996;88(4 Pt 2):739–44.8841285 | E6
Zhang X, Gao X, Hou R. Evaluation of the effect of midwife doula accompany nursing on nursing effect and pregnancy outcome of parturient in painless delivery. Minerva Surgery. 2021;17:17. | E10
Zielinski RE, Brody MG, Low LK. The Value of the Maternity Care Team in the Promotion of Physiologic Birth. J Obstet Gynecol Neonatal Nurs. 2016;45(2):276–84. | E4

### APPENDIX C EVIDENCE TABLES

#### CHARACTERISTICS OF INCLUDED PRIMARY STUDIES

Randomized Controlled Studies

Observational Studies

#### OUTCOME DATA OF INCLUDED PRIMARY STUDIES

Randomized Controlled Studies

Observational Studies

#### QUALITY ASSESSMENT OF INCLUDED PRIMARY STUDIES

Randomized Controlled Trials

Observational Studies

#### STRENGTH OF EVIDENCE FOR INCLUDED STUDIES

### APPENDIX D PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | n/a
2 | 2 | Yes | n/a
3 | 3 | Yes | n/a
4 | 4 | Yes | n/a
Is there any indication of bias in our synthesis of the evidence?
5 | 1 | No | n/a
6 | 2 | No | n/a
7 | 3 | No | n/a
8 | 4 | Yes - This is written more in terms of OB- led care, medical model of care, instead of Midwifery Model of Care- which is something that can be studied a little more. Might not be a bias per se. | Thank you, given the scope of work for this report, our report does focus primarily on a medical model of care, but as suggested, future research can benefit from studying other models of care.
Are there any published or unpublished studies that we may have overlooked?
9 | 1 | Yes - For a review on implementation considerations check BMC Pregnancy Childbirth 2017 Aug 31;17(1):265. doi: 10.1186/s12884-017-1447-9. | Thank you, we have reviewed this study and incorporated it into our report as it pertains to implementation.
10 | 2 | No | n/a
| 3 | No | n/a
12 | 4 | Yes - Not sure if these are primary sources of studies, but the Listening to Mothers I and II studies is an excellent resource to go back to look at quality of care for birthing people. Evidence Based Birth synthesizes lots of research (Cochrane and otherwise) into research papers- highly recommend just seeing what research papers they reference in their research on the Evidence for Doulas. | Thank you, we used the Evidence-based Birth website to hand search additional studies that met our study inclusion criteria.; Thank you for recommending the DeClerq and Sakala publications of the Listening to Mothers I & II studies, these studies did not fit the scope of our current report which specifically examined clinically important maternal and neonatal outcomes.
Additional suggestions or comments can be provided below.
13 | 1 | Page 5, line 50-53: giving birth with the support of a doula is presented as an alternative mode of childbirth which it isn’t. Having a birth companion of choice is a global recommended practice and it needs to be presented as such and not as an alternative. | Thank you, we have removed the word “alternative” and reworded this section to the following:; “Additionally, birth companions or doulas can provide complementary continuous labor support throughout a pregnancy and are a globally recommended model of care. Doulas act as companions to the pregnant individual and provide a range of reproductive care services depending on their degree of training and the clinical care setting”
14 | 1 | Doula is typically defined as a trained professional who provides emotional and physical support during childbirth and beyond and who is not medically trained. It appears that any form of support during labor and birth provided by anyone outside of the medial team caring for the woman is considered a doula support in this document. Doula is a profession that has identifiable functions and training. It is important to make the differentiation in this document otherwise the purpose of the evidence synthesis remains unclear. I suggest using labor and birth companionship or birth companions rather than doula support considering the evidence that is reviewed includes interventions that evaluated the effectiveness of professional doulas as well as other lay companions during childbirth. | Thank you for your feedback. For the purposes of this report and the needs of our operational partners, we did define doula support in terms of trained/certified doulas vs. lay persons who provided birth companionship. As you have pointed out, the profession itself has very specific functions and training, however the available published literature we identified that met our scope and inclusion did not always clearly define the birth companion role and did often use the doula label in their studies. As a result, we felt it was important to retain those labels but have tried to provide enough details in our evidence tables for the reader to help them understand the context in which each study took place.
15 | 1 | In general, synthesis of findings from previous studies and the categorization of strength of evidence must take into consideration the power of the studies reviewed. It is necessary to go beyond the number of studies found in the literature reporting on the outcome of interest and looking the strength of the findings in individual studies. | Thank you for your feedback, we have conducted a strength of evidence assessment of all included studies which is available in the supplementary materials section of this report. We also rated the quality of individual studies and took that into consideration in our strength of evidence rating. We were unable rate precision in most studies due to lack of reporting of power and lack of information on what constitutes a clinically meaningful difference in outcomes. Our findings align closely with that of previously published systematic reviews for the outcomes of interest in this report.
16 | 1 | Following-up on the previous point, the decision on the effectiveness of birth companionship should emanate from studies with designs that provide valid findings on effectiveness such as RCTs. The authors in this systematic review need to rely on previous meta-analysis in this topic to draw conclusions on effectiveness of continuous support on health and birth outcomes (See Bohren Cochrane Database Syst Rev. 2017 Jul; 2017(7) ) | Thank you for your comment, a large proportion of our included studies were RCTs, and we have referenced Bohren 2017 in our report, as well as included all relevant studies in our synthesis. Our findings also align with the meta-analysis conducted by Bohren et al.
17 | 1 | The relationship of continuous support during childbirth with maternal mortality can be indirect. As women are more likely to use facilities for childbirth when they are encouraged to have birthing companions, this will increase the likelihood of having access to life saving interventions during childbirth and thus reduce maternal mortality. | Thank you for your comment. While our findings showed an unclear correlation between doula support and maternal mortality, we do acknowledge that our results are limited to those studies that met our inclusion criteria, but we didn’t identify any studies attempting to measure mortality this way, thus our included studies were focused on direct measurement of maternal mortality.
18 | 2 | I find this report to be well-researched and unbiased. I anticipate that it will be of value to The Office of Women’s Health as we work to further support pregnant and postpartum Veterans. | Thank you for your feedback..
19 | 3 | Statement starting on line 33 starting with “although maternity care is not currently provided by VHA” is incorrect. VHA does provide maternity care through purchasing from the community. Recommend that the text be revised to better reflect that throughout the report. | Thank you for your comment, we have made this correction throughout the report.
20 | 3 | Consider revising the description of maternity care coordinators (MCCs) to be “to work with pregnant Veterans to ensure that they get the care and resources they need during pregnancy and postpartum.” This is important as the MCCs also help coordinate care that pregnant Veterans may be receiving in VA during pregnancy (e.g. mental health care). MCCs also are critical for ensuring that Veterans receive the lactation supplies that are included in the maternity care benefit (nursing bras, pump, pads, etc). Recommend that this text be revised throughout the report. | Thank you for your feedback. We have reworded this section, and throughout the report as follows:; “Maternity Care Coordinators (MCCs) are appointed to work with pregnant Veterans to ensure that they get the care and resources they need during pregnancy and postpartum, and to navigate their care with providers outside the VHA.^5^ MCCs are a critical resource for ensuring that Veterans receive the lactation supplies that are included in the maternity care benefit (ie. nursing bras, breast pumps, nursing pads, etc).”
21 | 3 | The paragraph starting on line 42 seems to misunderstand that doulas are never a replacement for a ob/gyn, certified nurse midwife, or community midwife. Their role is to provide emotional support, coaching, and sometimes education (e.g. birth education, parenting, etc). The most standard definition that I have found is “Doulas are non-medical persons that provide emotional, physical, and informational support for pregnant people before, during and after labor, often coaching clients to self-advocate in medical settings.” Thus, they can be present in the context of any birth setting (hospital, home birth, independent birth center). While doulas a typically an independent service paid and contracted by the pregnant person, more recently hospital based doula programs have been implemented. | Thank you, we have removed the word “alternative” and reworded this section to the following:; “Additionally, birth companions or doulas can provide complementary continuous labor support throughout a pregnancy and are a globally recommended model of care. Doulas act as companions to the pregnant individual and provide a range of reproductive care services depending on their degree of training and the clinical care setting”
22 | 3 | A missing bit is providing the reader with a brief explanation of why avoiding labor interventions such as Pitocin may be preferable. This literature is pretty complex w lots of methodologic issues, but it is important to point out that basically birth in the US is highly medicalized, expensive, with worse outcomes then other high income nations. One contributor to the poor outcomes is thought to be the overmedicalization and overuse of interventions. Recommend referencing the ACOG Committee Opinion Number 766 Approaches to Limit Intervention During Labor and Birth. | Thank you for pointing out the need for clarification of the reason for use of labor interventions as an outcome of interest. We have added the following text to address this:; “High rates of cesarean birth and the use of medical interventions during labor in the U.S are associated with significant morbidity and mortality. One of the leading causes of primary cesarean delivery is arrested labor, which in the hospital setting is often addressed with the use of oxytocin.^15^ It has been proposed that doula care may lead to reduced use of oxytocin or epidural analgesia; Supportive care during labor may enhance physiological labor processes and maternal feelings of agency and confidence in the birthing person’s ability to successfully navigate the labor, thereby reducing the need for labor interventions.^14^”
23 | 3 | The objective is stated to cover maternal, infant and delivery outcomes. However, no clear definition/differentiation of these is made. In particular Table ES-1 presents findings in no particular order with respect to outcome. Recommend throughout the report to clearly and consistently define and order these outcomes. Figure 1 begins to do this, but it mixes maternal and delivery outcomes. These either should be consistently one set or separated. I would lean towards lumping into a single category. | Thank you for your comment, the ES and subsequent results and summary of findings are ordered in accordance with the key questions laid out in the report. We have added sub headers in the table to help clearly delineate between outcome groups.
24 | 3 | Unclear why studies that took place in low income countries where the context of birth is very different were included. If these are retained then I recommend including something in the limitations about this and separating these from the studies that occurred in high-income countries. | Thank you for your comment, we have added the following comment to the discussion regarding low-income/developing countries:; “..some studies were conducted in developing countries while others were in higher-income countries in which the context of birth is very different. Given the scope and purpose of this review, this review focused on characteristics of doula support and outcomes of interest without consideration to healthcare system and healthcare access.”
25 | 4 | comment on Acknowledgements: Fatima Abdallah, DTI (am not a DONA doula, but rather a DTI doula or you can use the letter CD (Certified Doula) | Thank you, we have made the correction.
26 | 4 | Page 5, line 51- don’t use alternative, only use complementary. Doulas are not an alternative to the OBs, but are part of complementary care. Alternatively, if you wanted to discuss alternatives in the future or add something more inclusive, midwifery care is an alternative to OB based care- usually ideal for low risk pregnancies, and can be provided in a hospital or out of hospital birth space. Topic for a different paper. Doula care on the other hand, is complentary care to both types of obstetrical care; that provided by either OBs or midwives. | Thank you for your comment, we have reworded this section to read as follows:; “Contemporary maternal labor and delivery (L&D) care often equates to a hospital-based birth with a team of obstetrical medical providers. A complementary care model is the use of a birth companion or doula which is a globally recommended practice providing continuous labor support throughout a pregnancy, often in concert with obstetric care. Doulas act as companions to the pregnant individual and provide a range of reproductive care services depending on their degree of training and the clinical care setting”
27 | 4 | Page 16, line 9/10: description of doula support-instead of just emotional support, doula support can be described as emotional, informational, physical support | Thank you for your comment, we did not limit our inclusion to only emotional support and included all types of support in our report.
28 | 4 | page 30, line 8-9: What is a doula trained nurse midwife? That doesn’t make sense. A nurse midwife is a completely different field than a doula’s but there is often confusion about this. Nurse-midwives actually take on role of OB more than than of a doula. They are medically trained personnel with a focus on low risk pregnancies and birth care. | Thank you for that clarification. We have reworded this to read as “nurse/midwife with doula training” to reference those described in the literature as labor staff who received additional training to provide supportive doula services.
29 | 4 | Page 30, line 27: Just a note- more often, doulas work as independent of the hospital system, and specifically hired by the pregnant family. This helps keep them aligned with the preferences of their clients, and not influenced by hospital policies if they might go against preferences of the pregnant individual. It allows for advocacy of pregnant person’s values and preferences. | Thank you, we inserted this additional information into Table 2.
30 | 4 | page 104 line 28, last column- doula midwife is not a designation. A doula is not a midwife. Perhaps this was a term used in research paper; as in a midwife also with doula training? | Yes, that is correct, the authors of Feng 2013 used the term “doula midwife” to describe the labor companion for participants in their observational study (p. 574):; “In the observation group, from initial labouring to two hours postpartum, each primipara was accompanied with one Doula midwife. During the delivery accompanying process, Doula midwife conducted psychological, physiological, and physical care, and explained delivery-related concepts to primiparas and their families and provided mental and spiritual support”; Source: Feng, B. B., Wang, L., & Zhai, J. J. (2013). Investigation on delivery analgesia effect of combined spinal epidural anesthesia plus Doula and safety of mother and baby. Clinical and Experimental Obstetrics & Gynecology, 40(4), 574–578 24597260
31 | 4 | page 139 line 29- doulas do not contradict medical personnel, but one way to help families receive the model of care they desire is to offer midwifery services as well as obstetrical services. Many families might feel like their preferences in a birth are better served by one model of care vs the other. Once they are in a space that is in line with their preferences, it helps overall. There are two models of care for birth-Midwifery model of care and Medical or Active Management of Labor. Doulas help show alternatives and options in care from one provider to another, and that gives clients an ability to choose which model of care is more in line with their preferences. | Thank you for this additional insight into the doula scope of practice, we have added this context into Appendix F.
32 | 4 | page 139, line 60- Many top-notch doula orgs not included here, another one is DTI- Doula Trainings International | Thank you, in the interest of brevity we were unable to provide a comprehensive list of organizations, but we have now included DTI in our supplementary materials.

### APPENDIX E PROFESSIONAL DOULA STANDARDS

As of 2022, there is no state licensure for doulas and certification is not standardized – based on surveillance conducted in 2018, only 23 states contained hospitals that had implemented any kind of doula service agreement/policy;^46^ however, many state agencies have begun to implement programs that would provide access to doula support for those with less financial means, including state funded Medicaid programs. Hospitals that regularly work with doula services or have hospital-based doula care have made doula certification a requirement.^47–51^

#### SCOPE OF PRACTICE^52^

Planning assistance: Help parents make informed choices based on what they value. A doula does not give medical advice or perform any medical tasks. The doula may describe the procedure, explain why it is done, clarify the procedure’s risks and benefits, and offer alternatives.

Provide resources: Connect families with additional resources and support. When clients have questions about medical issues, the doula can consider this an opportunity to facilitate communication between the client and their caregivers. When the birthing person and their family speak directly with their health care providers, it reduces risk of miscommunication and promotes informed decision-making.

Facilitate effective communication between families and healthcare team: Doulas do not contradict health care providers. Entering an adversarial relationship with that provider undermines the woman’s confidence in her provider and in her ability to make her own choices.

One way to help families receive the model of care they desire is to offer midwifery services as well as obstetrical services. Many families might feel like their preferences in a birth are better served by one model of care versus the other. Once they are in a space that is in line with their preferences, it helps overall.

There are two models of care for birth- Midwifery model of care and Medical or Active Management of Labor: doulas provide their clients with information on both models to help them make an informed choice.

#### REQUIRED COURSEWORK & CORE COMPETENCIES^52,53^

- Physiology of childbirth; - Common interventions and evidence-based care; - Comfort measures for Childbirth; - Breastfeeding; - Anatomy and cervical change during labor; - The emotional impact of labor and birth; - Bishop score, induction of labor, and medical interventions | - The stages of labor and how doulas support each phase; - Communicating with medical care providers and clients utilizing emotional intelligence; - Hospital birth and home birth; - Hormones associated with labor; - Physical comfort measures and emotional support | - Cesarean birth and emergency situations; - The Golden Hour and how to support it; - Breastfeeding; - Family bonding; - Newborn assessments and medications; - The client/doula relationship; - Doula contracts and business basics

#### US-BASED CERTIFICATION ORGANIZATIONS

Doulas of North America (DONA) | https://www.dona.org/become-a-doula/birth-doula-certification/
Doula Trainings International (DTI) | https://doulatrainingsinternational.com/
International Childbirth Education Association (ICEA) | https://icea.org/certification/icd-exam/
International Doula Institute | https://internationaldoulainstitute.com/birth-doula-certification-program/ (https://internationaldoulainstitute.com/birth-doula-certification-program/?sfw=pass1646512518)
ProDoula | https://www.prodoula.com/labor-doula-trainings/

### APPENDIX F RESEARCH IN PROGRESS

Status | Study Title | Study Design | Information Resources
Recruiting | EngagINg the COmmunity to Reduce Preterm Birth Via Adherence to an Individualized Prematurity Prevention Plan (INCORPorATe IP3) | Prospective cohort | ClinicalTrials.gov Identifier: NCT04933812
Enrolling by invitation | Growing Together: Expanding Knowledge About and Evaluating Services for Incarcerated Pregnant and Postpartum Women in Arkansas | Non-randomized controlled trial (allocation based on self-selection) | ClinicalTrials.gov Identifier: NCT04421235
Recruiting | Today Not Tomorrow Pregnancy and Infant Support Pro Record #7 | Non-randomized controlled trial (allocation based on self-selection) | ClinicalTrials.gov Identifier: NCT04879797
Recruiting | Randomized Controlled Trial to Evaluate Efficacy of Psychological Support Based on Positive Suggestions (PSBPS) on Mental Health Morbidity and Cognitive Function | Open-label cluster RCT | ClinicalTrials.gov Identifier: NCT04100577
Not yet recruiting | Mobilizing Doulas to Empower Women in Post-partum Diabetes Prevention, a Randomized Controlled Trial | Single-blinded RCT | ClinicalTrials.gov Identifier: NCT04406792
Active, not recruiting | Pilot Study of ICU Doulas Providing Psychological Support Based on Positive Suggestions to Mitigate Psychological and Cognitive Sequelae of Critical Illness | Prospective cohort | ClinicalTrials.gov Identifier: NCT03736954
Not yet recruiting | Reducing Racial Disparities in SMM: Assessing the Integration of Maternal Safety Bundles and Community Based Doulas to Improve Outcomes for Black Women | Non-randomized controlled trial (allocation based on locations) | ClinicalTrials.gov Identifier: NCT04879797
Not yet recruiting | Well-Mama Community Doula Navigator Study (Enhancing Perinatal Care Support to Improve Maternal Mortality Disparities) | Open-label RCT | ClinicalTrials.gov Identifier: NCT05179369
In progress | Cooperation Between Midwives and Doulas in Context of Perinatal Care – A Systematic Review of Qualitative and Quantitative Studies | Systematic review | PROSPERO; ID: CRD42020182428; https://www.crd.york.ac.uk/PROSPERO/
In progress | Community-Based Doulas for Migrant Women: A Systematic Review and Narrative Synthesis | Systematic review | PROSPERO; ID: CRD42020193216; https://www.crd.york.ac.uk/PROSPERO/
In progress | Doula Support for Minority and Disadvantaged Women: A Meta-Analysis of Observational Studies | Meta-analysis | PROSPERO; ID: CRD42020209563; https://www.crd.york.ac.uk/PROSPERO/
In progress | Childbirth and Psychological Outcomes of Doula Support: A Systematic Review and Meta-Analysis | Systematic review/meta-analysis | PROSPERO; ID: CRD42020222764; https://www.crd.york.ac.uk/PROSPERO/
In progress | The Influence of Support People, Including the Partner and Care-Providers, and the Use of Antenatal Education Information and Techniques During Labour and Birth. A Meta-Synthesis. | Systematic review/meta-analysis | PROSPERO; ID: CRD42021275614; https://www.crd.york.ac.uk/PROSPERO/

Abbreviations: ICU=intensive care unit; PROSPERO=international prospective register of systematic reviews; RCT=randomized controlled trial; SMM=severe maternal morbidity.

### REFERENCES

1 Bolbol-Haghighi N, Masoumi SZ, Kazemi F. Effect of Continued Support of Midwifery Students in Labour on the Childbirth and Labour Consequences: A Randomized Controlled Clinical Trial. Journal of Clinical and Diagnostic Research JCDR. 2016;10(9):QC14–QC17.
2 Campbell DA, Lake MF, Falk M, Backstrand JR. A randomized control trial of continuous support in labor by a lay doula. J Obstet Gynecol Neonatal Nurs. 2006;35(4):456–464.
3 Cogan R, Spinnato JA. Social support during premature labor: effects on labor and the newborn. Journal of Psychosomatic Obstetrics & Gynecology. 1988;8(3):209–216.
4 Dickinson JE, Paech MJ, McDonald SJ, Evans SF. The impact of intrapartum analgesia on labour and delivery outcomes in nulliparous women. Australian and New Zealand journal of obstetrics and gynaecology. 2002;42(1):65–72.
5 Gagnon AJ, Waghorn K, Covell C. A randomized trial of one-to-one nurse support of women in labor. Birth. 1997;24(2):71–77.9271971
6 Gagnon AJ, Waghorn K. One-to-one nurse labor support of nulliparous women stimulated with oxytocin. J Obstet Gynecol Neonatal Nurs. 1999;28(4):371–376.
7 Gordon NP, Walton D, McAdam E, Derman J, Gallitero G, Garrett L. Effects of providing hospital-based doulas in health maintenance organization hospitals. Obstetrics & Gynecology. 1999;93(3):422–426.10074992
8 Hans SL, Edwards RC, Zhang Y. Randomized Controlled Trial of Doula-Home-Visiting Services: Impact on Maternal and Infant Health. Maternal & Child Health Journal. 2018;22(Suppl 1):105–113.29855838
9 Hodnett ED, Lowe NK, Hannah ME, . Effectiveness of nurses as providers of birth labor support in North American hospitals: a randomized controlled trial. JAMA. 2002;288(11):1373–1381.12234231
10 Hofmeyr GJ, Nikodem VC, Wolman W-L, Chalmers BE, Kramer T. Companionship to modify the clinical birth environment: effects on progress and perceptions of labour, and breastfeeding. BJOG: An International Journal of Obstetrics & Gynaecology. 1991;98(8):756–764.
11 Isbir GG, Sercekus P. The Effects of Intrapartum Supportive Care on Fear of Delivery and Labor Outcomes: A Single-Blind Randomized Controlled Trial. Journal of Nursing Research. 2017;25(2):112–119.
12 Kashanian M, Javadi F, Haghighi MM. Effect of continuous support during labor on duration of labor and rate of cesarean delivery. International Journal of Gynecology & Obstetrics. 2010;109(3):198–200.20152972
13 Kennell J, Klaus M, McGrath S, Robertson S, Hinkley C. Continuous emotional support during labor in a US hospital. A randomized controlled trial. JAMA. 1991;265(17):2197–2201.2013951
14 Klaus MH, Kennell JH, Robertson SS, Sosa R. Effects of social support during parturition on maternal and infant morbidity. British Medical Journal Clinical Research Ed. 1986;293(6547):585–587.3092934
15 Langer A, Campero L, Garcia C, Reynoso S. Effects of psychosocial support during labour and childbirth on breastfeeding, medical interventions, and mothers’ wellbeing in a Mexican public hospital: a randomised clinical trial. British Journal of Obstetrics & Gynaecology. 1998;105(10):1056–1063.9800927
16 Lesser PA, Maurer M, Stephens S, Yolkut R. Doulas for all. International Journal of Childbirth Education. 2005;20(3):28–32.
17 Madi BC, Sandall J, Bennett R, MacLeod C. Effects of female relative support in labor: a randomized controlled trial. Birth. 1999;26(1):4–8.10352048
18 McGrath SK, Kennell JH. A randomized controlled trial of continuous labor support for middle-class couples: effect on cesarean delivery rates. Birth. 2008;35(2):92–97.18507579
19 Morhason-Bello IO, Adedokun BO, Ojengbede OA. Social support during childbirth as a catalyst for early breastfeeding initiation for first-time Nigerian mothers. International Breastfeeding Journal. 2009;4:7p–7p.19607695
20 Ravangard R, Basiri A, Sajjadnia Z, Shokrpour N. Comparison of the Effects of Using Physiological Methods and Accompanying a Doula in Deliveries on Nulliparous Women’s Anxiety and Pain: A Case Study in Iran. Health Care Manager. 2017;36(4):372–379.28961642
21 Safarzadeh A, Beigi M, Salehian T, Khojasteh F, Burayri T, Navabirigi S. Effect of doula support on labour pain and outcomes in primiparous women in Zahedan, southeastern Iran: a randomized controlled trial. J Pain Relief. 2012;1(5):2167-0846.1000112.
22 Trueba G, Contreras C, Velazco MT, Lara EG, Martinez HB. Alternative strategy to decrease cesarean section: support by doulas during labor. Journal of Perinatal Education. 2000;9(2):8–13.17273201
23 Yuenyong S, O’Brien B, Jirapeet V. Effects of labor support from close female relative on labor and maternal satisfaction in a Thai setting. J Obstet Gynecol Neonatal Nurs. 2012;41(1):45–56.
24 Austad K, Juarez M, Shryer H, Moratoya C, Rohloff P. Obstetric care navigation: results of a quality improvement project to provide accompaniment to women for facility-based maternity care in rural Guatemala. BMJ Quality & Safety. 2020;29(2):169–178.
25 Byrskog U, Small R, Schytt E. Community-based bilingual doulas for migrant women in labour and birth - findings from a Swedish register-based cohort study. BMC Pregnancy & Childbirth. 2020;20(1):721.33228571
26 Chen CC, Lee JF. Effectiveness of the doula program in Northern Taiwan. Tzuchi Medical Journal. 2020;32(4):373–379.
27 Dundek LH. Establishment of a Somali doula program at a large metropolitan hospital. Journal of Perinatal & Neonatal Nursing. 2006;20(2):128–137.16714912
28 Feng BB, Wang L, Zhai JJ. Investigation on delivery analgesia effect of combined spinal epidural anesthesia plus Doula and safety of mother and baby. Clinical & Experimental Obstetrics & Gynecology. 2013;40(4):574–578.24597260
29 Fulton JM. Doula Supported Childbirth: An Exploration of Maternal Sensitivity, Self-Efficacy, Responsivity, and Parental Attunement, University of California, Davis; 2011.
30 Gadappa SN, Deshpande SS. A Quasi-Experimental Study to Compare the Effect of Respectful Maternity Care Using Intrapartum Birth Companion of Her Choice on Maternal and Newborn Outcome in Tertiary Care Centre. Journal of Obstetrics & Gynaecology of India. 2021;71(Suppl 2):84–89.34924719
31 Goedkoop V. Side by side -- a survey of doula care in the UK in 2008. MIDIRS Midwifery Digest. 2009;19(2):217–218.
32 Gruber KJ, Cupito SH, Dobson CF. Impact of doulas on healthy birth outcomes. Journal of Perinatal Education. 2013;22(1):49–58.24381478
33 Kabakian-Khasholian T, Bashour H, El-Nemer A, Kharouf M, Elsheikh O, Labour Companionship Study G. Implementation of a labour companionship model in three public hospitals in Arab middle-income countries. Acta Paediatrica. 2018;107 Suppl 471:35–43.30570794
34 KC A, Axelin A, Litorp H, Tinkari BS, Sunny AK, Gurung R. Coverage, associated factors, and impact of companionship during labor: A large-scale observational study in six hospitals in Nepal. Birth. 2020a;47(1):80–88.31765037
35 Kozhimannil KB, Hardeman RR, Attanasio LB, Blauer-Peterson C, O’Brien M. Doula care, birth outcomes, and costs among Medicaid beneficiaries. In. American Journal of Public Health. Vol 103 2013:e113–121.23409910
36 Kozhimannil KB, Attanasio LB, Jou J, Joarnt LK, Johnson PJ, Gjerdingen DK. Potential benefits of increased access to doula support during childbirth. American Journal of Managed Care. 2014;20(8):e340–352.25295797
37 Mottl-Santiago J, Walker C, Ewan J, Vragovic O, Winder S, Stubblefield P. A hospital-based doula program and childbirth outcomes in an urban, multicultural setting. In. Maternal & Child Health Journal. Vol 12 2008:372–377.17610053
38 Nommsen-Rivers LA, Mastergeorge AM, Hansen RL, Cullum AS, Dewey KG. Doula care, early breastfeeding outcomes, and breastfeeding status at 6 weeks postpartum among low-income primiparae. J Obstet Gynecol Neonatal Nurs. 2009;38(2):157–173.
39 Shelp A. Women helping women: the Somali Doula Initiative. International Journal of Childbirth Education. 2004;19(4):4–7.
40 Spiby H, Green, J. M., Darwin, Z., Willmot, H., Knox, D., McLeish, J., & Smith, M. Multisite implementation of trained volunteer doula support for disadvantaged childbearing women: a mixed-methods evaluation. Centre for Reviews and Dissemination. 2015.
41 Thomas MP, Ammann G, Brazier E, Noyes P, Maybank A. Doula Services Within a Healthy Start Program: Increasing Access for an Underserved Population. Maternal & Child Health Journal. 2017;21(Suppl 1):59–64.29198051
42 Kozhimannil. Doula care, birth outcomes, and costs among Medicaid beneficiaries. 2013.
43 Shalev J. Having a doula during labor and delivery. Midwifery Today & Childbirth Education. 1992(24):8–9.
44 Zhang Y, Johnston L, Ma D, Wang F, Zheng X, Xu X. An exploratory study of the effect of labor pain management on postpartum depression among Chinese women. Ginekologia Polska. 2018;89(11):627–636.30508215
45 Berkman ND, Lohr KN, Ansari MT, . Grading the strength of a body of evidence when assessing health care interventions: an EPC update. J Clin Epidemiol. 2015;68(11):1312–1324.25721570
46 Baracker L. HAL, Lingas, E.O., Burroes S. Examining Hospital Doula Policies: An analysis of doula within Maternal Child Health in the U.S. [Conference Presentation]. Paper presented at: 2018 Annual meeting of the American Public Health Association2018; San Diego, CA.
47 Gray S. UMMS, VA launch first ever VA study of women’s maternal health care. In. Vol 2022. UMass Chan Medical School 2016.
48 Veterans Authority. Pilot Program For Tricare to Cover Doulas, Lactation Consultants Begin. 2021.
49 ACOG. Safe Prevention of the Primary Cesarean Delivery. Consensus Statement of the American College of Obstetricians and Gynecologists and the Society for Maternal-Fetal Medicine. 2014.
50 Military.com. Tricare Maternity Care For Active Duty and Separating Families. https://www.military.com/benefits/tricare/tricare-maternity-care-options.html#:~:text=Active%20duty%20service%20members%20are%20expected%20to%20receive,a%20local%20civilian%20hospital%20for%20the%20actual%20delivery (https://www.military.com/benefits/tricare/tricare-maternity-care-options.html#:%7E:text=Active%20duty%20service%20members%20are%20expected%20to%20receive,a%20local%20civilian%20hospital%20for%20the%20actual%20delivery). Published 2022. Accessed February 2022.
51 Department of Veteran Affairs. Women Veterans Health Care. https://www.womenshealth.va.gov/WOMENSHEALTH/OutreachMaterials/GeneralHealthandWellness/maternity.asp. Published 2022. Accessed February 2022.
52 DONA International. Position Paper: The Birth Doula’s Role in Maternity Care. 2016.
53 ICEA. Certification Information,. https://icea.org/certification/icea-certification-philosophy-and-programscertification/. Published 2022. Accessed February 2022.