# Evidence Brief: Transcranial Magnetic Stimulation (TMS) for Chronic Pain, PTSD, TBI, Opioid Addiction, and Sexual Trauma

## Preface

The VA Evidence Synthesis Program (ESP) was established in 2007 to provide timely and accurate syntheses of targeted healthcare topics of importance to clinicians, managers, and policymakers as they work to improve the health and healthcare of Veterans. These reports help:

- Develop clinical policies informed by evidence;
- Implement effective services to improve patient outcomes and to support VA clinical practice guidelines and performance measures; and
- Set the direction for future research to address gaps in clinical knowledge.

The program is composed of three ESP Centers across the US and a Coordinating Center located in Portland, Oregon. Center Directors are VA clinicians and recognized leaders in the field of evidence synthesis with close ties to the AHRQ Evidence-based Practice Center Program and Cochrane Collaboration. The Coordinating Center was created to manage program operations, ensure methodological consistency and quality of products, and interface with stakeholders. To ensure responsiveness to the needs of decision-makers, the program is governed by a Steering Committee composed of health system leadership and researchers. The program solicits nominations for review topics several times a year via the program website (https://www.hsrd.research.va.gov/publications/esp/TopicNomination.cfm).

Comments on this evidence report are welcome and can be sent to Nicole Floyd, Deputy Director, ESP Coordinating Center at Nicole.Floyd@va.gov.

## EXECUTIVE SUMMARY

#### Purpose

The ESP Coordinating Center is responding to a request from the Center for Compassionate Care Innovation for an evidence brief on the use of transcranial magnetic stimulation (TMS) for the treatment of mental and physical health diagnoses (not including major depressive disorder). Findings from this evidence brief will be used to inform a VHA pilot program to provide access to TMS for Veterans suffering from chronic pain, post-traumatic stress disorder (PTSD), traumatic brain injury (TBI), opioid addiction, or sexual trauma as required by HR 1162, “No Hero Left Untreated Act”. The goal of this review is to synthesize important and recent evidence on TMS effectiveness and safety for treatment of chronic pain, PTSD, TBI, opioid addiction, and sexual trauma.

#### Methods

To identify studies, we searched MEDLINE®, Cochrane Database of Systematic Reviews, Cochrane Central Register of Controlled Trials, and other sources up to August 2020. We used prespecified criteria for study selection, data abstraction, and rating internal validity and strength of the evidence. See our PROSPERO protocol for our full methods.

#### Key Findings

- Most studies of transcranial magnetic stimulation (TMS) therapy employed repetitive TMS (rTMS). rTMS may reduce symptoms in people with chronic pain, post-traumatic stress disorder (PTSD), traumatic brain injury (TBI), and opiate addiction, but findings are mixed among included studies.
- rTMS could be a treatment option for patients who have exhausted other available options for treatment of chronic pain, PTSD, TBI, opiate addiction, but practical aspects of more widely implementing TMS in a healthcare system need to be considered.
- Future research should focus on studies with larger samples, robust methodology, and standardized TMS parameters.

Transcranial magnetic stimulation (TMS) is a noninvasive therapy that uses coils to pass magnetic pulses through the skull to induce electrical currents. These currents stimulate the underlying brain cortex. TMS therapy can vary based on the types of coils used, the brain area stimulated, the frequency and intensity of the magnetic pulses, and the number and speed of pulses delivered. The most common therapeutic use of TMS is for treatment of major depressive disorder (MDD), and the FDA began approving various devices for this application in 2008.

Since approval for MDD, TMS has been investigated for treatment of other conditions, including traumatic brain injury (TBI), post-traumatic stress disorder (PTSD), pain, schizophrenia, dementia, and substance use disorder. Compared to MDD, fewer studies have examined the efficacy of TMS for these conditions, and there remain open questions about the generalizability of existing evidence, the reliability of treatment effects, and the optimal treatment protocol for each condition.

Based on evidence from 39 included controlled studies, our review suggests that repetitive TMS (rTMS), the most common form of TMS therapy, may be effective for treating chronic pain, PTSD, TBI, and opiate addiction (Table ES-1). However, there were inconsistent findings among studies, and about half of included studies found that reduction in chronic pain, PTSD, and TBI symptoms did not significantly differ between TMS therapy and sham therapy control groups. No studies specifically examined TMS as a therapy for sexual trauma, and no studies directly compared rTMS to novel forms of TMS such as theta-burst or electroencephalogram (EEG)-guided TMS.

Despite the mixed effectiveness findings, TMS was found to be a safe and generally well-tolerated therapy.

There was considerable variation in patient populations (demographics, disease or symptom characteristics, etc), TMS protocols (TMS coil type and position, stimulation parameters, etc), and study methodology (sample size, outcomes and number of timepoints assessed, etc), among the included studies. This variation may contribute to the inconsistency in the observed effects of TMS therapy. Moreover, the generally small sample sizes of studies could have limited statistical power to detect differences between TMS and control conditions.

Practical aspects of more widely implementing TMS in a health care system need further consideration, particularly as they relate to patient and provider burden, cost, and accessibility. TMS therapy generally consists of daily therapy, usually for a period of 4 to 6 weeks, and patients must travel daily to a designated clinic where TMS is offered. TMS therapy also requires assessment by a trained physician to determine if TMS therapy is appropriate and to prescribe the therapy. Limitations in transportation or clinic access for patients, staff availability, training requirements, and the need for a designated clinic site with TMS technology may be barriers in expanding use of TMS.

Pairing these considerations with the findings that suggest potential effectiveness and high patient safety and acceptability, it is reasonable to conclude that TMS therapy, in particular rTMS, could be considered a treatment option for patients who have exhausted other available options for treatment of chronic pain, PTSD, TBI, or opiate addiction. With this approach, a limited expansion of rTMS could be conducted, which would provide additional information about implementation feasibility and would allow for more rigorous trials to be conducted.

Table ES-1 Summary of Findings

Condition | Evidence | Summary
Chronic Pain | 17 controlled studies; 14 rTMS, 3 iTBS; Low to Moderate SOE | rTMS and iTBS may reduce pain, but inconsistent findings among studies
PTSD | 10 RCTs; 8 rTMS, 1 iTBS, 1 sTMS; Low SOE | rTMS and sTMS may reduce PTSD symptoms, but inconsistent findings among studies
TBI | 10 controlled studies^*^; Low SOE | rTMS may improve symptoms after TBI, but inconsistent findings among studies
Opiate Addiction | 2 RCTs^*^; Moderate SOE | rTMS likely improves opiate craving in adults with heroin addiction
Sexual Trauma | 0 studies | –

* All included studies examined rTMS

Abbreviations: rTMS=repetitive transcranial magnetic stimulation; iTBS=intermittent theta-burst TMS; SOE=strength of evidence; PTSD=post-traumatic stress disorder; RCT=randomized controlled trial; sTMS=synchronized TMS; TBI=traumatic brain injury

## INTRODUCTION

### PURPOSE

The ESP Coordinating Center (ESP CC) is responding to a request from the Center for Compassionate Care Innovation for an evidence brief on the use of transcranial magnetic stimulation (TMS) for the treatment of mental and physical health diagnoses (not including major depressive disorder). Findings from this evidence brief will be used to inform a VHA pilot program to provide access to TMS for Veterans suffering from chronic pain, post-traumatic stress disorder (PTSD), traumatic brain injury (TBI), opioid addiction, or sexual trauma as required by HR 1162, “No Hero Left Untreated Act”.^1^

### BACKGROUND

#### What is Transcranial Magnetic Stimulation?

TMS is a noninvasive therapy that uses magnetic pulses to induce electrical currents in various parts of the brain.^2^ TMS was introduced in 1985,^3^ and has been used in a variety of applications, including for intraoperative neurologic monitoring,^4^ to investigate nerve conduction, to diagnose neurologic conditions,^5^ and for the treatment of psychiatric and neurologic conditions. Therapeutic use of TMS involves placing an insulated coil over various areas of the scalp and passing magnetic pulses through the skull and into the brain.^6^ The exact biological mechanism of TMS is unknown, but it is hypothesized that as magnetic pulses pass through the skull, electrical activity is induced in nerve cells, activating underlying areas of the brain cortex.^3,7^ This induced activity may alter synaptic plasticity, or the ability of nerve cell connections to strengthen or weaken over time.^8^ Biological studies have shown changes in neural activity with TMS treatment, including increased blood flow and dopamine transmission in areas of the brain targeted by TMS.^3^

TMS therapy can vary based on the types of coils used, the brain area stimulated, the frequency and intensity of the magnetic pulses, and the number and speed of pulses delivered. Depending on the type of coil used, magnetic pulses can be delivered over large regions or more focused areas of the brain. The most common coil types are circular coils, figure-8 coils, and H-coils.^9^ The multiple layers of coils inside the H-coil helmet allow for deeper stimulation (~4 cm) into the brain compared to conventional circular or figure-8 coils, which can stimulate about 1 cm into the brain.^10^ Additionally, different areas of the brain can be targeted by placing the coil over different locations of the scalp. Common locations for stimulation include the primary motor cortex and dorsolateral prefrontal cortex (DLPFC), with variation in placement over the right hemisphere, left hemisphere, or midline.^11,12^

The magnetic pulses during TMS therapy can be delivered at different frequencies (measured in Hertz [Hz]) and intensities. Low frequency (< 5 Hz) stimulation has inhibitory effects on neural activity in the brain, while high frequency (≥ 5 Hz) stimulation has excitatory effects.^9^ The intensity of TMS therapy is often individualized, and is set at a proportion of an individual’s motor threshold (described as the strength of stimulus required to produce movement of the thumb or fingers). Intensities set at more than 100% of this threshold may have greater risk of adverse events, including seizure.^3^ However, typically MDD TMS protocols treat at 100-120% of RMT without significant side effects in most patients.^13^ TMS therapy can also vary based on the number and duration of magnetic pulses delivered. Repetitive TMS (rTMS) delivers magnetic pulses to the brain rapidly at regular intervals and is the most widely studied and commonly used type of TMS. Alternatively, TMS can be delivered as a single pulse, where 1 pulse occurs no faster than once every few seconds.^14^

Novel TMS therapies proposed to enhance the therapeutic effect of TMS include theta-burst TMS (iTBS), synchronized TMS (sTMS), and electroencephalogram (EEG)-guided TMS. Theta-burst TMS delivers either an intermittent or continuous triple-pulse magnetic stimulation, which is hypothesized to induce longer-lasting therapeutic effects. It is delivered at a higher frequency (~50 Hz) than rTMS (~5-10 Hz) and requires shorter TMS sessions (~3 minutes vs ~20-30 minutes). In synchronized TMS, magnetic fields are synchronized to a person’s intrinsic alpha frequency using multiple magnets. EEG-guided TMS involves placing the TMS coil over an EEG cap so that brain activity can be measured during TMS therapy, allowing for real-time assessment of the optimal TMS parameters.^5^ Another form of EEG-guided TMS, Magnetic eResonance Therapy (MeRT^SM^),^15^ involves recording and analyzing a patient’s EEG at various time points during the course of treatment to develop a tailored TMS treatment plan. It is unclear whether these forms of TMS offer improved outcomes over rTMS.

#### Therapeutic Uses for Transcranial Magnetic Stimulation

The most common therapeutic use of TMS is for treatment of depression. In 2008, the first rTMS device for treatment of major depressive disorder (MDD) was approved by the FDA,^16^ and several other devices have since been cleared for this use.^17^ Numerous studies have shown benefits of rTMS therapy in patients with depression, including decreases in depression symptom severity, and greater response and remission rates among patients with the use of rTMS compared to sham TMS.^7,18^ There are various treatment protocols for rTMS for depression, but a typical protocol may be daily (5 days/week) 20 to 40 minute rTMS sessions over a period of 4 to 8 weeks, with each session delivering 3,000 to 6,000 pulses at 10 Hz.^3^ The American Psychiatric Association and National Network of Depression Centers rTMS Task Group issued guidance for clinicians to help navigate the variety of rTMS protocols available for the treatment of depression.^13^ This guidance outlines recommendations for coil selection and placement, magnetic field intensity and frequency (Hz), and number and duration of pulses. Additionally, it is recommended to assess patients for risk factors, including history of stroke or seizure, alcohol and drug use, sleep deprivation, and any side effects of previous rTMS use, prior to implementing rTMS and again at each session.^13^

Since approval for MDD, rTMS has been investigated for treatment of other conditions, including TBI,^19–21^ PTSD,^22–27^ pain,^28,29^ schizophrenia,^24,30^ dementia,^22^ and substance use disorder.^22,31,32^ The FDA expanded the approved marketing of rTMS for treatment of certain headaches in 2013 and for obsessive-compulsive disorder (OCD) in 2018.^17^ Compared with MDD, fewer studies have examined the efficacy of TMS for these conditions, and there remain open questions about the generalizability of existing evidence, the reliability of treatment effects, and the optimal treatment protocol for each condition.

#### Usage of TMS in the VHA

TMS therapy in the VHA is offered through the National Clinical rTMS program, which began in 2017 as an effort to expand access to rTMS therapy for Veterans.^33^ There are currently 35 VA rTMS clinics across the US, with additional clinics under development. Currently, rTMS is most commonly used within the VHA for treatment of depression, and the VA/DoD guideline for major depressive disorder recommends offering rTMS during a major depressive episode in patients with treatment-resistant MDD.^34^ There is interest in expanding the use of TMS to treat other conditions, including TBI, PTSD, chronic pain, opioid addiction, and sexual trauma, but the evidence on the use of TMS therapy for these conditions among Veterans is less established. VA/DoD guidelines for PTSD,^34^ mild TBI (tinnitus after mild TBI, update in progress),^34^ and headache^34^ state that there is insufficient evidence to recommend for or against the use of rTMS for treatment of these conditions (supplemental materials Appendix A).

The goal of this evidence brief is to synthesize important and recent evidence on TMS effectiveness and safety for treatment of chronic pain, PTSD, TBI, opioid addiction, and sexual trauma. The review is intended to inform development of a TMS program for treatment of Veterans with these conditions.

### KEY QUESTIONS

Key Question 1: What is the effectiveness of TMS for the treatment of post-traumatic stress disorder, traumatic brain injury, sexual trauma, chronic pain, or opioid addiction?

Key Question 2: What are the potential adverse effects of using TMS for the treatment of post-traumatic stress disorder, traumatic brain injury, sexual trauma, chronic pain, or opioid addiction?

Key Question 3: Do the effectiveness and potential adverse effects of TMS differ according to patient or intervention characteristics (eg, patient demographics, comorbidities, disease severity, TMS frequency)?

### ELIGIBILITY CRITERIA

The ESP included studies that met the following criteria:

- [underlined: P]opulation: Adults with post-traumatic stress disorder, traumatic brain injury, sexual trauma, chronic pain, or opioid addiction
  - [underlined: I]ntervention: Transcranial magnetic stimulation (eg, repetitive, theta-burst, EEG-guided, EKG-guided, or combination EEG/EKG guided)
  - [underlined: C]omparator: Any
  - [underlined: O]utcomes: Symptom improvement (eg, response, remission), mortality, quality of life, adverse events (eg, headache, worsening symptoms, nausea, seizure)
  - [underlined: T]iming: Any
  - [underlined: S]etting: Any
  - [underlined: S]tudy design: Using a best-evidence approach, we will prioritize evidence from systematic reviews and multisite comparative studies that adequately controlled for potential patient-, provider-, and system-level confounding factors. Inferior study designs (eg, single-site, inadequate control for confounding, noncomparative) will only be accepted to fill gaps in higher-level evidence

## METHODS

### DATA SOURCES AND SEARCHES

To identify articles relevant to the key questions, our research librarian searched MEDLINE (Ovid), CINAHL (EBSCO), PsycINFO (Ovid), and CENTRAL (Ovid) databases as well as AHRQ, CADTH, Cochrane, VA HSR&D, and Clinicaltrials.gov websites using terms for transcranial magnetic stimulation, post-traumatic stress disorder, traumatic brain injury, opioid disorders, and sexual trauma from January 2012 to August 2020. We located an existing systematic review on TMS and chronic pain^35^ with an end search date in 2017, so we searched the same databases using terms for transcranial magnetic stimulation and chronic pain from January 2017 to August 2020 (see Appendix B in supplemental materials for full search strategies). Because of the large number of citations for chronic pain, we excluded pain areas that were of low interest to the report nominators (bladder pain, hemiplegic shoulder pain, and orofacial pain). Additional citations were identified from hand-searching reference lists and consultation with content experts. We limited the search to published and indexed articles involving human subjects available in the English language. Study selection was based on the eligibility criteria described above. Titles and abstracts and full-text articles were reviewed by 1 reviewer and checked by another. All disagreements were resolved by consensus or discussion with a third reviewer.

### DATA ABSTRACTION AND QUALITY ASSESSMENT

We used predefined criteria to rate the internal validity of all controlled studies. We used Cochrane’s Risk of Bias Tools to rate the internal validity of systematic reviews and concurrently controlled studies.^36–38^ We abstracted data from all included studies and results for each included outcome. All data abstraction and internal validity ratings were first completed by 1 reviewer and then checked by another. All disagreements were resolved by consensus.

### SYNTHESIS

Strength of evidence (SOE) grading was based on the AHRQ Methods Guide for Comparative Effectiveness Reviews,^39^ by considering risk of bias (includes study design and aggregate quality), consistency, directness, and precision of the evidence. Ratings typically range from high to very low, indicating our confidence that the evidence reflects an unbiased and precise estimate of the true effect. For this review, we applied the following general algorithm: evidence composed of multiple, large studies with low risk of bias were rated as “high strength” evidence, evidence composed of multiple studies with low to unclear risk of bias and consistent findings were rated as “moderate strength”, evidence composed of single studies, or multiple small studies with unclear to high risk of bias and/or inconsistent findings were rated as “low strength”, and evidence composed of a single study with high risk of bias was rated as “very low strength”. These criteria were applied to primary outcomes for all conditions. Because quality of life was inconsistently reported as a primary or secondary outcome in TBI-related studies, strength of evidence was evaluated for any quality of life outcome reported by these studies. Strength of evidence ratings were completed by 1 reviewer and checked by another. We synthesized the evidence qualitatively by condition, prioritizing controlled studies.

A draft version of this report was reviewed by peer reviewers as well as clinical leadership (see supplemental materials for disposition of peer review comments). The complete description of our full methods can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42020202648).

## RESULTS

### LITERATURE FLOW

The literature flow diagram (Figure 1) summarizes the results of the study selection process (full list of excluded studies available in supplemental materials, Appendix C).

Figure 1 Literature Flowchart

*In 56 publications (1 study with 2 publications)

CCRCT=Cochrane Register of Controlled Trials, CINAHL=Cumulative Index to Nursing and Allied Health Literature, SR = systematic review

Our search identified 1,729 potentially relevant articles. We included 55 studies: 1 systematic review (see Appendix D in supplemental materials for primary studies included in this review),^35^ 39 controlled studies (in 40 publications),^40–79^ and 15 case series.^80–94^ The majority of the controlled studies were in populations with chronic pain (n = 17), PTSD (n = 10), or TBI (n = 10). Two studies were identified in patients with opiate addiction,^71,95^ and no studies were identified in patients with sexual trauma. We also identified 39 ongoing studies (see Appendix E in supplemental materials for details), 13 for chronic pain, 7 for PTSD, 5 for TBI, and 14 for opiate addiction. Most studies investigated rTMS (N=34), but several studies examined use of intermittent theta-burst stimulation (iTBS)^54,70,48,67^ or synchronized TMS (sTMS)^65^ (Figure 2).

Figure 2 Overview of Included Controlled Studies

Abbreviations: rTMS=repetitive TMS; PTSD=post-traumatic stress disorder; TBI=traumatic brain injury, iTBS=intermittent theta-burst TMS; sTMS=synchronized TMS

Most of the included controlled studies were RCTs (N=34), with follow-up ranging from 1 week to 7 months (Table 1). TMS protocols varied widely by TMS target location, frequency and intensity of stimulation, and number and duration of sessions (for full study details see Appendix F in supplemental materials). Sham TMS most often consisted of a “sham coil” which mimicked the vibrations and sounds of the TMS coil, or placement of the TMS coil at 90° away from the skull.

Most studies had unclear risk of bias (N=24) (supplemental materials, Appendix G) and common study limitations were unclear or inappropriate handling of missing outcome data, lack of reporting of study follow-up or withdrawal, unclear allocation concealment, and self-reported outcomes (Figure 3). Self-reported outcomes were considered a potential risk of bias, given that self-reporting may be subject to bias and is unblinded by definition. However, because most outcomes assessed in the primary studies were, by necessity, self-reported (eg, change in severity of pain, opiate cravings, or PTSD symptoms), use of self-reported measures was not considered sufficient to increase the overall risk rating of studies (eg, from low to unclear overall risk).

Table 1 Characteristics of Included Controlled Studies

Author, Year N | Study Design Follow-up | Population | Intervention | Primary Outcome(s) | TMS Protocol
Author, Year N | Study Design Follow-up | Population | Intervention | Primary Outcome(s) | Location | Frequency Intensity | # Sessions
Chronic Pain: Neuropathic
Ahmed, 2020^41^; N=30 | RCT; 1 week | Patients with a diagnosis of diabetic neuropathy | rTMS and aerobic training exercises | Pain | Precentral motor cortex | 20 Hz; 80-90% RMT | 5 sessions (daily)
Andre-Obadia, 2018^43^; N=35 | Randomized crossover trial; NR | Patients with upper limb or facial neuropathic pain | rTMS | Pain | Hand or facial motor cortex | 20 Hz; 90% RMT | 3 sessions (2 active, 1 sham)
Galhardoni, 2019^49^; N=100 | RCT; 12 weeks | Patients with chronic central neuropathic pain | Deep rTMS | Pain | ACC or PSI | 10 Hz; 90% RMT | 16 (daily for 5 days, then 1 session/wk for 11 wks)
Hosomi, 2020^51^; N=144 | RCT; 5 weeks | Adult patients with neuropathic pain | rTMS | Pain | Primary motor cortex | 5 Hz; 90% RMT | 5 sessions (daily), then 1 session/wk for 4 wks (responders only)
Kim, 2020^54^; N=30 | RCT; 7 months | Patients with CNP | iTBS | Pain | Ipsilateral hemisphere | 50 Hz; 80% RMT | 5 sessions (daily)
Quesada, 2020^68^; N=42 | Randomized crossover trial; 7 months | Adult patients with medically refractory chronic central neuropathic pain | rTMS | Pain | Primary motor cortex | 20 Hz; 80% RMT | 8 sessions over 9 wks
Shimizu, 2017^72^; N=18 | Randomized crossover trial; 3 months | Patients with intractable neuropathic pain in lower limbs | Deep rTMS or rTMS | Pain | Primary motor cortex | 5 Hz, 90% RMT | 15 (5 consecutive sessions with each type of stimulation)
Sun, 2019^79^; N=21 | RCT; 6 weeks | Right-handed inpatient rehab patients with neuropathic pain following SCI | rTMS | Pain | Left primary motor cortex | 10 Hz; 80% RMT | Daily sessions for 6 weeks, with 1-day interval per week
Chronic Pain: Fibromyalgia
Abd Elghany, 2019^76^; N=120 | nRCT; 1 month | Outpatients with FMS | rTMS | Pain | DLPFC | 10 Hz; NR | 15 sessions (every other day for 1 month)
Atlas, 2019^42^; N=30 | RCT; 3 weeks | Right-handed, female patients with FMS | rTMS | Pain | Left primary motor cortex or left DLPFC | 10 Hz; 90% RMT | 15 (5 sessions/wk for 3 wks)
Bilir, 2020^44^; N=20 | RCT; 6 weeks | Adult patients with diagnosis of FMS | rTMS | Pain | Left DLPFC | 10 Hz; 90% RMT | 14 (5 days/wk for 2 wks, then 1 session/wk for 4 wks)
Cheng, 2019^45^; N=20 | RCT; 2 weeks | Patients with FMS and MDD | rTMS | Pain | Left DLPFC | 10 Hz; 100% RMT | 10 (5 sessions/wk for 2 wks)
Fitzgibbon, 2018^77^; N=26 | RCT; 1 month | Patients with FMS | rTMS | Pain | Left DLPFC | 10 Hz; 120% RMT | 20 (5 consecutive sessions/wk for 4 wks)
Guinot, 2019^50^; N=39 | RCT; 6 months | Patients with FMS | rTMS + multicomponent therapy | Pain | Primary motor cortex | 10 Hz; 80% RMT | 5 sessions/wk for 2 wks, then 12-wk decreasing maintenance phase
Chronic Pain: Headache
Mattoo, 2019^63^; N=30 | RCT; 8 weeks | Right-handed patients with history of headache >15 days a month for 3 months or more | rTMS | Pain | Right DLPFC | NR; 110% RMT | 20 (5 sessions/wk for 4 wks)
Sahu, 2019^70^; N=41 | RCT; 2 weeks | Right-handed patients with a diagnosis of migraine with or without aura | iTBS | Headache symptoms | Left DLPFC | 50 Hz; 80% RMT | 10 (2x/day for 5 days)
Chronic Pain: Complex Regional Pain Syndrome
Gaertner, 2018^48^; N=21 | Cohort; 2 weeks | Patients with CPRS | iTBS followed by TMS | Pain | Motor cortex to stimulate CPRS affected region | 50 Hz (iTBS) then 10 Hz (TMS); 70% (iTBS) then 80% (TMS) | 1 or 5 sessions over 5 days
PTSD
Ahmadizadeh, 2018^40^; N=65 | RCT; 4 weeks | Veterans with current combat-related PTSD symptoms | rTMS | PTSD symptoms | Bilateral or right DLPFC | 20 Hz; 100 % RMT | 10 (3 sessions/wk for 2 wks then 2 sessions/wk for 2 wks)
Fryml, 2019^47^; N=8 | RCT; 8 weeks | Veterans (OIF/OEF) with combat-related PTSD | rTMS and Prolonged exposure therapy (PE) | PTSD symptoms | Right or left prefrontal cortex | 10 Hz; 120% RMT | 8 (1 session/wk for 8 wks)
Isserles, 2013^53^; N=30 | RCT; 4 weeks | Veterans with PTSD | Deep rTMS + traumatic imagery | PTSD symptoms | Prefrontal cortex | 20 Hz; 120% RMT | 12 (3 sessions/wk for 4 wks)
Kozel, 2018^55^; N=103 | RCT; 6 months | Veterans deployed to combat regions, 2001-present | rTMS + cognitive processing therapy | PTSD symptoms | Right DLPFC | 1 Hz; 110% RMT | 12 (1 session/wk for 12 wks)
Kozel, 2019^56^; N=35 | RCT; 3 months | Veterans with PTSD with and without depressive symptoms | rTMS | PTSD symptoms | Right DLPFC | 1 Hz or 10 Hz; 110% RMT | 36 (timing NR)
Leong, 2020^58^; N=31 | RCT; 3 months | Civilians with non-combat related PTSD | rTMS | PTSD symptoms | Right DLPFC | 1 Hz or 10 Hz; 120% RMT | 10 (5 sessions/wk for 2 wks)
Nam, 2013^64^; N=18 | RCT; 8 weeks | Patients with non-military related PTSD | rTMS | PTSD symptoms | Right prefrontal cortex | 1 Hz; 100% RMT | 15 (5 consecutive sessions/wk for 3 wks)
Petrosino, 2020^65,*^; N=46 | RCT; 1 year | Veterans with PTSD | iTBS | Clinical relapse | Right DLPFC | 50 Hz; 80% RMT | 10 sessions (5 consecutive sessions/wk for 2 weeks)
Philip, 2019^67,*^; N=50 | RCT; 1 month | Veterans with PTSD | iTBS | PTSD symptoms | Right DLPFC | 50 Hz; 80% RMT | 10 sessions (5 consecutive sessions/wk for 2 weeks)
Philip, 2019^66^; N=23 | RCT; 8 weeks | People with PTSD and MDD | Synchronized TMS (sTMS) | PTSD symptoms | NR | NR; NR | 20 (5 sessions/wk for 4 wks)
Watts, 2012^75^; N=20 | RCT; 10 weeks | People with PTSD | rTMS | PTSD symptoms | Right DLPFC | 1 Hz; 90% RMT | 10 sessions (5 consecutive days/wk for 2 wks)
TBI
Choi, 2018^46^; N=12 | RCT; 6 weeks | Adults with mild TBI and pain lasting ≥ 6 months | rTMS | Pain | Primary motor cortex | 10 Hz; 90% RMT | 10 sessions (5 per wk for 2 wks)
Hoy, 2019^52^; N=21 | RCT; 4 weeks | People with TBI with current depressive episode | rTMS | Depression symptoms | Left or right DLPFC | 1 Hz (right), 10 Hz (left); 110% RMT | 20 sessions (over 4 wks)
Lee, 2018^57^; N=13 | RCT; 2 weeks | Patients with TBI without severe depression | rTMS + neurodevelopmental therapy | Depression symptoms | Right DLPFC | 1 Hz; 100% RMT | 10 (5 consecutive sessions/wk for 2 wks)
Leung, 2016^59^; N=24 | RCT; 4 weeks | Veterans with mild TBI and post-traumatic headache | rTMS (targeted by neuronavigated TMS) | Headache symptoms | Left motor cortex | 10 Hz; 80% RMT | 3 sessions (within 1 wk)
Leung, 2018^60^; N=29 | RCT; 4 weeks | Veterans with mild TBI related headache | rTMS (targeted by neuronavigated TMS) | Headache symptoms | Left prefrontal cortex | 10 Hz; 80% RMT | 4 sessions (within 1 wk)
Manko, 2013^62^; N=40 | nRCT; NR | People with severe TBI and prolonged coma | rTMS | Mental and physical comfort | NR | NR; NR | NR
Neville, 2019^78^; N=36 | RCT; 90 days | People with chronic TBI | rTMS | Change in executive function | Left DLPFC | 10 Hz; 110% RMT | 10 sessions (daily)
Rao, 2019^69^; N=34 | RCT; 16 weeks | People with TBI and MDD | rTMS | Depressive symptoms | Right DLPFC | 1 Hz110% RMT | 20 (5 consecutive sessions/wk for 4 wks)
Siddiqi, 2019^73^; N=12 | RCT; NR | People with TBI and TRD | rTMS (targeted by resting-state network mapping) | Depressive symptoms | Left and right DLPFC | 1 Hz (right), 10 Hz (left); 120% RMT | 20 sessions (over 5 wks)
Stilling, 2020^74^; N=20 | RCT; 6 months | People with post-TBI headache | rTMS | Headache symptoms | Left DLPFC | 10 Hz; 70 % RMT | 10 (5 consecutive sessions/wk for 2 wks)
Opiate Addiction
Liu, 2020^61^; N=118 | RCT; 90 days | Male heroin use disorder patients | rTMS | Craving score: Subjective 0-100 scale | Left DLPFC | 10 Hz or 1 Hz; 100% RMT | 20 sessions over 28 days
Shen, 2016^71^; N=20 | RCT; 5 days | Heroin addicted adults | rTMS | Craving score: Subjective 0-100 scale | Left DLPFC | 10 Hz; 100% RMT | 5 sessions (daily)

* Petrosino, 2020 and Philip, 2019 are two reports of the same study.

Abbreviations: TMS=Transcranial magnetic stimulation; RCT= Randomized controlled trial; rTMS=Repetitive transcranial magnetic stimulation; Hz=Hertz; RMT=Resting motor threshold; ACC=Anterior cingulate cortex; PSI=Posterior superior insula; nRCT=non-randomized controlled trial, DLPFC=Dorsolateral prefrontal cortex; CNP =Central neuropathic pain; iTBS=Intermittent theta-burst stimulation, SCI=Spinal cord injury; MDD=Major depressive disorder; TRD=Treatment resistant depression; wk/wks = week/weeks

Figure 3 Risk of Bias in Included Randomized Controlled Trials

### CHRONIC PAIN

#### Overall Pain Reduction

A 2018 Cochrane systematic review^35^ examined the use of non-invasive brain stimulation therapies for chronic pain. Forty-two studies on the effect of rTMS for pain were included. These studies measured pain severity using visual analog scales (VAS) or numerical rating scales (NRS). Overall, meta-analyses showed a significant reduction in pain associated with rTMS within 7 days post-intervention (SMD = −0.22, 95% CI [−0.29, −0.16]; 27 studies). Reductions in pain were also observed between 1 and 6 weeks post-intervention (SMD = −0.28, 95% CI [−0.61, 0.05]; 11 studies) and at greater than 6 weeks post-intervention (SMD = −0.14, 95% CI [−0.44, 0.17]; 4 studies), but these effects were nonsignificant. Significant improvement in reported quality of life (Fibromyalgia Impact Questionnaire) was observed within 7 days post-intervention (SMD = −10.8, 95% CI [−15.04, −6.55]; 4 studies). Minor and brief-duration adverse effects were commonly reported across studies and included headache, pain at stimulation site, and dizziness. Studies varied by type of pain conditions included and rTMS protocols used. Study quality was rated mostly as “unclear” and was limited by unclear blinding of participants (inadequate sham), small sample size, and short study duration.

Our search identified 17 controlled studies published since the end search date of this systematic review.^35^ Findings from these studies are discussed by pain type, below.

#### Neuropathic Pain

rTMS therapy may reduce pain (measured by VAS or NRS) in patients with neuropathic pain, but the evidence is limited by inconsistent findings, and unclear or lack of blinding of patients or outcome assessors, and unclear or inadequate handling of missing data in several studies. Among 8 controlled trials, 5 studies^43,54,68,72,79^ reported reduction in pain with TMS compared to sham TMS, while 3 studies^41,49,51^ reported no significant difference in pain between TMS and sham groups. In the 2 largest trials (N=100;^49^ N=144^51^), no significant difference was found between rTMS and sham groups in pain reduction. Most studies reported shorter-term outcomes (1 to 6 weeks), but 3 studies reported outcomes at 3 to 7 months (1 study no pain reduction,^49^ 2 studies pain reduction^68,72^ compared to sham). A single study compared iTBS to sham iTBS,^54^ and all other studies utilized rTMS. Studies varied with respect to pain areas (upper limb, lower limb, central neuropathic pain, etc), types of TMS (2 studies deep TMS,^49,72^ 1 study intermittent theta-burst TMS^54^) and TMS protocols (target location, frequency, intensity, and number of sessions). Evidence from 3 case series^88,89,92^ generally agreed with trial findings, indicating reductions in pain over time with TMS therapy.

#### Fibromyalgia

In patients with fibromyalgia syndrome, rTMS therapy may be no better than sham rTMS therapy in reducing overall pain symptoms (measured by VAS or NRS).^42,44,45,76,50,77^ This evidence is limited by small sample sizes (4 of 6 studies had 30 or fewer participants) and lack of or inadequate randomization in several studies. Six controlled studies reported reduction in pain outcomes in both rTMS and sham rTMS groups, with generally no significant differences in outcomes between groups. However, several studies reported greater reduction of pain with rTMS therapy for specific rTMS target locations (reduction in pain with primary motor cortex vs sham but not left DLPFC vs sham),^42^ time points (reduction in pain with rTMS compared to sham at week 2 vs week 1, but no significant difference when comparing weekly pain scores),^45^ or outcomes (more patients achieving 30% reduction in pain in TMS group compared to sham group, but no significant difference in average pain reduction between groups).^77^ Most studies reported shorter-term outcomes (2 to 6 weeks), with the exception of 1 study reporting no significant reduction in pain at 6 months compared to control.^50^ All studies used rTMS and targeted either the primary motor cortex^42,50^ or the left DLPFC^42,44,45,77^ with 10 Hz stimulation at 80-100% RMT, but the number and duration of TMS sessions varied among the studies.

#### Headache

TMS therapy likely reduces headache pain and symptoms compared to sham TMS in patients with chronic headache or migraine,^63,70^ but the evidence is limited by small sample sizes, and non-random allocation and unclear handling of missing data in 1 study.^70^ Two studies reported decreases in pain (using NRS)^63^ or migraine frequency, severity, and duration^70^ at 8 to 12 weeks with rTMS therapy targeted to the right DLPFC^63^ or iTBS therapy targeted to the left DLPFC^70^ compared to sham.

#### Multiple or Other Pain Conditions

A single small cohort study and several case series examined multiple or other pain conditions. The cohort study^48^ reported reductions in pain (measured by VAS and NRS) in patients with complex regional pain syndrome with both 1 or 5 sessions of iTBS stimulation immediately followed by rTMS, with no differences between groups. Since all patients in this study received some type of TMS stimulation, it is not possible to determine the effectiveness of TMS compared to sham. Three case series reported reductions in pelvic pain^91,93^ and general pain (from multiple conditions)^90^ over time with TMS therapy. These studies are limited by a study design without a control group.

### POST TRAUMATIC STRESS DISORDER

rTMS therapy may improve PTSD symptoms compared to sham, but evidence is limited by inconsistent findings and methodological limitations, including unclear or inappropriate handling of missing data, differential attrition between intervention groups, and unclear blinding in several studies. Among 10 controlled studies (in 11 publications),^40,47,53,55,56,64–67,75,58^ most studies reported improvements in PTSD symptoms, as measured by the Clinician-Administered PTSD Scale (CAPS) or the PTSD Checklist (PCL). However, only 4 studies reported greater improvement in symptoms with TMS compared to sham. Among included studies, TMS protocols varied in target location, frequency, intensity, and number of sessions.

One study^40^ reported a greater proportion of responders (defined as 2 or more standard deviations from the mean PCL score) with rTMS compared to sham, but no significant difference in mean PCL improvement between groups. Six studies were in Veterans with PTSD,^40,47,53,55,56,67^ the largest of which (N=113)^55^ reported improved PTSD symptoms at 6 months with rTMS therapy compared to control. Only 2 other studies reported outcomes beyond 8 weeks, and these studies found no significant difference in PTSD symptoms at 3 months compared to control.^56,58^ Two studies compared different frequencies of rTMS stimulation: 1 study^55^ found improved CAPS score with both 1 Hz and 10 Hz stimulation, but no significant difference between groups, while another study^58^ found improved CAPS score with 1 Hz rTMS compared to sham, but not with 10 Hz rTMS compared to sham. Several case series^80,82,84–87,94^ generally agreed with findings of randomized trials, reporting improvements in PTSD symptoms with rTMS therapy over time.

Two RCTs examined the effect of theta-burst TMS (iTBS)^65,67^ or synchronized TMS (sTMS),^66^ and found no significant differences between groups on PCL or CAPS scores at 2 to 4 weeks following treatment. In the study of sTMS, however, significantly fewer PCL items (symptoms) were rated as moderate or higher severity among participants receiving sTMS compared to sham 4 weeks post-treatment. The iTBS study also examined clinical relapse – defined as suicide attempt, suicide-related death, inpatient psychiatric hospitalization, or need for retreatment with rTMS – at 1 year and found that fewer patients had clinical relapse with iTBS compared to sham.^65^ One case series^82^ examined EEG-guided magnetic resonance therapy (MeRT^SM^) and reported improvement in PTSD symptoms after treatment. We also identified 1 RCT (abstract only)^96^ that reported improvement in PTSD symptoms in 8 subjects with use of MeRT^SM^, but there was no significant difference in outcomes between MeRT^SM^ and sham therapy.

### TRAUMATIC BRAIN INJURY

rTMS therapy may improve symptoms after TBI, but evidence is limited by inconsistent findings, small sample sizes, and unclear blinding of outcome assessors and unclear or inadequate handling of missing data in several studies. TBI can result in lasting cognitive sequelae, mood sequelae, and other symptoms, and we included any study that examined the effects of TMS on any symptom subsequent to any severity (mild, moderate, or severe) TBI. Included studies reported on a variety of symptoms following TBI, including pain, depressive symptoms, headache, and executive function. Most studies included patients with mild to moderate TBI,^46,57,59,60,69,73,74^ but 3 studies^52,62,78^ included patients with severe TBI exclusively or along with other TBI severity levels.

rTMS therapy improved headache symptoms,^60,74,83^ and overall pain (using NRS)^46^ compared to sham therapy in patients with TBI. Two studies in Veterans^60,83^ reported improvement in headache symptoms after mild TBI at 4 weeks with rTMS compared to sham therapy, while another study reported no significant difference in headache symptoms with rTMS after mild TBI compared to sham therapy at 6 months in a sample of patients from Canada.^74^ Four studies^52,57,69,73^ reported improved depressive symptoms with rTMS therapy after mild to moderate TBI, but there were no significant differences between rTMS and sham therapy in 3 of the 4 studies. One study^69^ reported no significant difference in rates of depression response or remission after mild to moderate TBI between rTMS and sham groups.

Seven studies examined the effect of rTMS therapy on executive function in patients after mild to severe TBI.^52,57,60,69,74,78,83^ Most studies found some improvement in function, but only 2 studies reported differences between rTMS and sham groups.^57,83^ Several studies^46,62,74^ also examined the effect of rTMS on quality of life. Most studies reported improvements in quality of life overall, but only one study reported significant differences between rTMS and sham therapy.^62^

Most studies reported outcomes at 2 to 6 weeks, but 3 studies reported no significant difference in TBI symptoms at 3 to 6 months compared to control.^69,74,78^ All studies examined rTMS, but varied in target location, frequency, intensity, and number of sessions. Two case series^81,83^ generally agreed with these findings, reporting improvements in post-concussive symptoms and pain with rTMS therapy over time.

### OPIATE ADDICTION

In adults with heroin addiction, rTMS therapy likely improves craving scores compared to sham therapy.^61,71^ Only 2 studies examined the effectiveness of rTMS for opiate use, and these studies are limited by unclear blinding of outcome assessors and/or participants and unclear handling of missing data. Both studies reported decreases in craving scores (0 to 100 craving scale) with rTMS therapy targeting the left DLPFC at 10 Hz and 100% resting motor threshold compared to sham rTMS. These studies assessed rTMS effects at different timepoints, ranging from 5 days after treatment^71^ to 90 days after treatment.^61^

### ADVERSE EFFECTS OF TMS

TMS therapy appears to be well-tolerated among patients with chronic pain, PTSD, TBI, and opiate addiction. About half of the included studies reported mild side effects including headache, nausea, pain at the target location, and dizziness, and 8 studies^40,48,55,56,58,61,68,69^ reported withdrawal of a small number of patients from the study due to side effects. No serious adverse events were reported in any included studies.

## SUMMARY AND DISCUSSION

rTMS therapy is widely used for treatment of MDD, and there is interest in expanding its use for other conditions including chronic pain, PTSD, TBI, opiate addiction, and sexual trauma. Our review of recent studies and systematic reviews suggests that rTMS therapy may be effective for treating chronic pain, PTSD, TBI, and opiate addiction. Importantly, however, about half of controlled studies examining the efficacy of TMS for reducing symptoms of chronic pain, PTSD, and TBI found that reduction in symptoms did not significantly differ between TMS and control groups (sham TMS). The majority of studies utilized rTMS, with few studies examining novel forms of TMS (eg, iTBS, sTMS, or EEG-guided TMS) and no studies directly compared rTMS to other forms of TMS.

Most studies examined differences in mean changes in outcome scores, which may yield statistically significant findings, but the magnitude of the difference may not translate into a clinically meaningful outcome for the patient. The 3 studies^56,69,77^ which examined symptom response or remission reported no significant difference between treatment and control groups in fibromyalgia pain,^77^ PTSD,^56^ or TBI^69^ symptom response or remission. Further, only 2 studies evaluated the efficacy of rTMS for opiate addiction,^61,71^ and no studies specifically examined TMS as a therapy for sexual trauma. Some patients with PTSD may have experienced sexual trauma, but less than half (4 of 10) of the included studies in patients with PTSD reported trauma history. Among these, only 2 studies listed patients with sexual trauma (range: 10 to 52% of patients). Further research on effectiveness of TMS among persons who have experienced sexual trauma, regardless of whether they have received a PTSD diagnosis, is needed.

In addition to these mixed or limited findings, there was considerable variation in patient populations, outcomes assessed, and TMS protocols implemented among the included studies. As a result, the effectiveness of TMS therapy may vary by patient factors (age, sex, sleep deprivation, etc) and technical factors (TMS coil type and position, stimulation parameters, etc).^97^ Reviewed studies also varied methodologically (eg, sample size, outcomes and number of timepoints assessed, etc), which could contribute to the inconsistency in the observed effects of TMS therapy. Moreover, the generally small sample sizes of studies could have limited statistical power to detect differences between TMS and control conditions. Despite the mixed effectiveness findings, TMS was found to be a safe and well-tolerated therapy.

Practical aspects of more widely implementing TMS in a healthcare system need further consideration, particularly as they relate to patient and provider burden, cost, and accessibility. TMS therapy generally consists of daily therapy, usually for a period of 4 to 6 weeks, and patients must travel daily to a designated clinic where TMS is offered. This may present challenges for Veterans living in rural areas or for those with transportation limitations. Although TMS therapy can be provided by a trained technician, a physician must perform a formal assessment to determine if TMS therapy is appropriate, followed by a prescription for the therapy. Limitations in staff availability, training requirements, and the need for a designated clinic site with TMS technology may be barriers in expanding the use of TMS.

Pairing these considerations with the findings that suggest potential effectiveness and high patient safety and acceptability, it is reasonable to conclude that TMS therapy, in particular rTMS, could be considered a treatment option for patients who have exhausted other available options for treatment of chronic pain, PTSD, TBI, and opiate addiction. A limited expansion of TMS for this purpose would provide further information about TMS implementation feasibility, while allowing additional efficacy and effectiveness trials to be conducted.

### LIMITATIONS

The evidence included in this review has several important limitations. Studies were mostly small, and varied in patient populations, outcomes, and TMS protocols, making generalizations of findings across studies difficult. Studies were also inconsistent in their methodological quality and findings, resulting in mostly low strength of evidence for the effect of TMS on chronic pain, PTSD, TBI, and opiate addiction (Table 2, Appendix H in supplemental materials). Additionally, although several studies followed patients for up to 7 months, most studies assessed outcomes at only 1 to 4 weeks. Without longer follow-up periods, the durability of symptom improvement following TMS remains unclear. Finally, no studies were found that specifically examined the effect of TMS among individuals who experienced sexual trauma or that examined differential effects of TMS among those with PTSD and sexual trauma compared to those with PTSD and other trauma history.

Limitations of our review methods include restricting our literature search date for chronic pain to the end search date of the O’Connell 2018^35^ review. Additionally, we used a second reviewer check during study selection, data abstraction, and quality assessment rather than dual independent review.

Table 2 Evidence Summary

Outcome | Studies (N) | Strength of Evidence (SOE) Summary
Chronic Pain: Neuropathic
Pain | 8 RCTs (N=420) 7 rTMS,^41,43,49,51,68,72,79^ 1 iTBS^54^ | Low SOE; rTMS may decrease pain compared to sham, but confidence is limited by inconsistent findings and low to high RoB among studies.
Chronic Pain: Fibromyalgia *
Pain | 5 RCTs (N=135)^42,44,45,50,77^ and 1 nRCT (N=120)^76^ | Low SOE; rTMS may be no better than sham in decreasing pain compared to sham, but confidence is limited by small sample sizes and low to high RoB among studies.
Chronic Pain: Headache
Headache pain and symptoms | 2 RCTs (N=71) 1 rTMS,^63^ 1 iTBS^70^ | Moderate SOE; TMS likely decreases headache pain and symptoms compared to sham but confidence is limited by small sample size and low to unclear RoB among studies.
PTSD
PTSD symptoms | 10 RCTs (N=383) 8 rTMS,^40,47,53,55,56,58,64,75^ 1 iTBS,^67^ 1 sTMS^66^ | Low SOE; rTMS may improve PTSD symptoms compared to sham, but confidence is limited by inconsistent findings and low to high RoB among studies.
Clinical relapse^**^ | 1 RCT (N=46), iTBS^65^ | Low SOE; iTBS may improve clinical relapse compared to sham, but confidence is limited by a single study.
TBI *
Pain | 1 RCTs (N=12)^46^ | Low SOE; rTMS may improve pain compared to sham, but confidence is limited confidence by a single, small study with unclear RoB.
Depression symptoms | 4 RCTs (N=83)^52,57,69,73^ | Low SOE; rTMS may improve depressive symptoms compared to sham, but confidence is limited by inconsistent findings and unclear RoB among studies.
Headache symptoms | 3 RCTs (N=73)^60,74,83^ | Low SOE; rTMS may improve headache symptoms compared to sham, but confidence is limited by inconsistent findings and low to unclear RoB among studies.
Quality of Life | 2 RCTs^46,74^ (N=32) and 1 nRCT (N=12)^62^ | Low SOE; It is unclear whether rTMS improves quality of life in patients with TBI, and confidence is limited by inconsistent findings and low to high RoB among studies
Function | 7 RCTs (N=177)^52,57,60,69,74,78,83^ | Low SOE; It is unclear whether rTMS improves function in patients with TBI, and confidence is limited by inconsistent findings and unclear RoB among studies
Opiate Addiction *
Craving Score | 2 RCTs (N=138)^61,71^ | Moderate SOE; rTMS likely improves craving scores in opiate addicted adults compared to sham, but confidence is limited by unclear RoB among studies.

1 cohort study, Gaertner 2018, examined iTBS for chronic regional pain syndrome, not included in table

* All studies examined rTMS

** Defined as suicide attempt, suicide-related death, inpatient psychiatric hospitalization, or need for rTMS retreatment

Abbreviations: SOE= Strength of Evidence, RCT= Randomized controlled trial, rTMS=Repetitive transcranial magnetic stimulation, iTBS= Intermittent theta-burst stimulation, RoB=Risk of Bias, nRCT=non-randomized controlled trial, PTSD=Post traumatic stress disorder, sTMS=Synchronized TMS; TBI=Traumatic brain injury

### GAPS AND FUTURE RESEARCH

Findings of this review suggest that it would be premature to conclude that TMS is an effective therapy for chronic pain, PTSD, TBI, and opiate addiction among Veteran populations. Additional studies with larger samples, robust methodology (ie, appropriate randomization and matching procedures), and standardized TMS parameters (ie, following various TMS guidance for specific patient populations, if available)^98^ are needed to provide more conclusive evidence. To address limitations to the existing evidence on the effectiveness of TMS for conditions other than MDD, future studies should consider the following:

- Although many RCTs were identified, most were small. This may be an inherent limitation to studies due to the cost of neurotherapies. However, greater resource investment would be beneficial to clarify the effectiveness of TMS for chronic pain, PTSD, TBI, and opiate addiction.
- No studies examined the use of TMS specifically for sexual trauma, and studies in this area are needed to determine the effectiveness of TMS therapy among individuals who have experienced sexual trauma.
- Studies directly comparing novel TMS therapy such as theta-burst or EEG-guided TMS to rTMS are needed to determine if these therapies offer any advantage over rTMS.

## CONCLUSIONS

rTMS therapy may reduce symptoms in people with chronic pain, PTSD, TBI, and opiate addiction and could be a treatment option for patients who have exhausted all other available options. However, findings are mixed and there is wide variability in patient and intervention characteristics among the included studies. Future research should focus on studies with larger samples, robust methodology, standardized TMS parameters, and direct comparisons of rTMS to novel TMS therapies (eg, iTBS, sTMS, or EEG-guided TMS). Practical aspects of more widely implementing TMS in a health care system, including patient and provider burden, cost, and accessibility, also need further consideration.

## ACKNOWLEDGMENTS

This review was developed in response to a nomination from the Center for Compassionate Care Innovation for an evidence review on the effectiveness and potential adverse effects of TMS for the treatment of post-traumatic stress disorder, traumatic brain injury, sexual trauma, chronic pain, or opioid addiction. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, and the review team.

The authors gratefully acknowledge the following individuals for their contributions to this project:

### Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Christine Eickhoff
  Health System Specialist
  10P10 Office of Community Engagement (OCE)

### Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.

## REFERENCES

1 No Hero Left Untreated Act.. Public Law 115-339 Web site. https://www.congress.gov/bill/115th-congress/house-bill/1162. Published 2018. Updated December 21, 2018. Accessed November 12th, 2020.
2 Perera T, George MS, Grammer G, Janicak PG, Pascual-Leone A, Wirecki TS. The clinical TMS society consensus review and treatment recommendations for TMS therapy for major depressive disorder. Brain stimulation. 2016;9(3):336–346.27090022
3 Aleman A. Use of repetitive transcranial magnetic stimulation for treatment in psychiatry. Clinical Psychopharmacology & Neuroscience. 2013;11(2):53–59.24023548
4 Barrett AM, Oh-Park M, Chen P, Ifejika NL. Neurorehabilitation: Five new things. Neurology Clinical Practice. 2013;3(6):484–492.24353922
5 Canadian Agency for Drugs and Technology in Health. Transcranial magnetic stimulation for the treatment of adults with PTSD, GAD, or depression: A review of clinical effectiveness and guidelines. Canadian Agency for Drugs and Technology in Health; 2015.
6 Transcranial Magnetic Stimulation (TMS) Service. Johns Hopkins Medicine. Psychiatry and Behavioral Sciences Web site. https://www.hopkinsmedicine.org/psychiatry/specialty_areas/brain_stimulation/tms/. Published 2020. Accessed October 21, 2020.
7 TMS Therapy. https://www.clinicaltmssociety.org/tms. Published 2020. Accessed October 21, 2020.
8 Zhengwu P, Cuihong Z, Shanshan X, . Mechanism of repetitive transcranial magnetic stimulation for depression. Shanghai archives of psychiatry. 2018;30(2):84.29736128
9 Klomjai W, Katz R, Lackmy-Vallée A. Basic principles of transcranial magnetic stimulation (TMS) and repetitive TMS (rTMS). Annals of physical and rehabilitation medicine. 2015;58(4):208–213.26319963
10 Tendler A, Barnea Ygael N, Roth Y, Zangen A. Deep transcranial magnetic stimulation (dTMS) - beyond depression. Expert Review of Medical Devices. 2016;13(10):987–1000.27601183
11 Peterchev AV, Wagner TA, Miranda PC, . Fundamentals of transcranial electric and magnetic stimulation dose: definition, selection, and reporting practices. Brain stimulation. 2012;5(4):435–453.22305345
12 Adamson MM. Rewiring the Brain: Zapping with Precision. Paper presented at: Cerebrum: the Dana Forum on Brain Science 2019.
13 McClintock SM, Reti IM, Carpenter LL, . Consensus recommendations for the clinical application of repetitive transcranial magnetic stimulation (rTMS) in the treatment of depression. The Journal of clinical psychiatry. 2017;79(1):0–0.
14 Galletta EE, Rao PR, Barrett AM. Transcranial magnetic stimulation (TMS): potential progress for language improvement in aphasia. Topics in stroke rehabilitation. 2011;18(2):87–91.21447455
15 Identify and Nurture (autism, PTSD, Sports Recovery, Depression). https://braintreatmentcenter.com/. Accessed October 21, 2020.
16 Melkerson M. Special premarket 510 (k) notification for NeuroStar TMS Therapy System for major depressive disorder. Food and Drug Administration. 2008;12:16.
17 FDA permits marketing of transcranial magnetic stimulation for treatment of obsessive compulsive disorder Food and Drug Administration. FDA News Release Web site. Published 2018. Updated August 17, 2018. Accessed October 21, 2020.
18 Gaynes BN, Lloyd SW, Lux L, . Repetitive transcranial magnetic stimulation for treatment-resistant depression: a systematic review and meta-analysis. The Journal of clinical psychiatry. 2014;75(5):477–489.24922485
19 Bhalerao SU, Geurtjens C, Thomas GR, Kitamura CR, Zhou C, Marlborough M. Understanding the neuropsychiatric consequences associated with significant traumatic brain injury. Brain Injury. 2013;27(7–8):767–774.23789861
20 Breceda EY, Dromerick AW. Motor rehabilitation in stroke and traumatic brain injury: stimulating and intense. Current Opinion in Neurology. 2013;26(6):595–601.24141528
21 Howard L, Schwedt TJ. Posttraumatic headache: recent progress. Current Opinion in Neurology. 2020;33(3):316–322.32304441
22 Bunse T, Wobrock T, Strube W, . Motor cortical excitability assessed by transcranial magnetic stimulation in psychiatric disorders: a systematic review. Brain Stimulation. 2014;7(2):158–169.24472621
23 Clark C, Cole J, Winter C, Williams K, Grammer G. A Review of Transcranial Magnetic Stimulation as a Treatment for Post-Traumatic Stress Disorder. Current Psychiatry Reports. 2015;17(10):83.26324821
24 Cristancho MA, Cristancho P, O’Reardon JP. Other therapeutic psychiatric uses of superficial brain stimulation. Handbook of Clinical Neurology. 2013;116:415–422.24112913
25 Ellis J, Zaretsky A. Assessment and Management of Posttraumatic Stress Disorder. CONTINUUM: Lifelong Learning in Neurology. 2018;24(3, BEHAVIORAL NEUROLOGY AND PSYCHIATRY):873–892.29851883
26 Gouveia FV, Gidyk DC, Giacobbe P, . Neuromodulation Strategies in Post-Traumatic Stress Disorder: From Preclinical Models to Clinical Applications. Brain Sciences. 2019;9(2):19.
27 Koek RJ, Roach J, Athanasiou N, van ’t Wout-Frank M, Philip NS. Neuromodulatory treatments for post-traumatic stress disorder (PTSD). Progress in Neuro-Psychopharmacology & Biological Psychiatry. 2019;92:148–160.30641094
28 DosSantos MF, Oliveira AT, Ferreira NR, Carvalho ACP, Rosado de Castro PH. The Contribution of Endogenous Modulatory Systems to TMS- and tDCS-Induced Analgesia: Evidence from PET Studies. Pain Research & Management. 2018;2018:2368386.30538794
29 Galhardoni R, Correia GS, Araujo H, . Repetitive transcranial magnetic stimulation in chronic pain: a review of the literature. Arch Phys Med Rehabil. 2015;96:(4 Suppl):S156–172.25437106
30 Aleman A, Enriquez-Geppert S, Knegtering H, Dlabac-de Lange JJ. Moderate effects of noninvasive brain stimulation of the frontal cortex for improving negative symptoms in schizophrenia: Meta-analysis of controlled trials. Neuroscience & Biobehavioral Reviews. 2018;89:111–118.29471017
31 Grall-Bronnec M, Sauvaget A. The use of repetitive transcranial magnetic stimulation for modulating craving and addictive behaviours: a critical literature review of efficacy, technical and methodological considerations. Neuroscience & Biobehavioral Reviews. 2014;47:592–613.25454360
32 Jansen JM, Daams JG, Koeter MW, Veltman DJ, van den Brink W, Goudriaan AE. Effects of non-invasive neurostimulation on craving: a meta-analysis. Neuroscience & Biobehavioral Reviews. 2013;37(10):2472–2480.23916527
33 Sierra Pacific (VISN 21) MIRECC. US Department of Veterans Affairs. TMS Education Overview Web site. Accessed October 21, 2020.
34 VA/DoD clinical practice guideline for the management of major depressive disorder. Management of Major Depressive Disorder Working Group,. Washington, DC: US Department of Veterans Affairs, US Department of Defense Web site. Published 2016. Accessed.
35 O’Connell NE, Marston L, Spencer S, DeSouza LH, Wand BM. Non-invasive brain stimulation techniques for chronic pain. Cochrane Database of Systematic Reviews. 2018;4:CD008208.
36 Whiting P, Savović J, Higgins J, . ROBIS: Tool to assess risk of bias in systematic reviews. Guidance on How to Use ROBIS. 2015.
37 Jüni P, Loke Y, Pigott T, . Risk of bias in non-randomized studies of interventions (ROBINS-I): detailed guidance. Br Med J. 2016.
38 Sterne JA, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. bmj. 2019;366.
39 Berkman ND, Lohr KN, Ansari M, . Grading the Strength of a Body of Evidence When Assessing Health Care Interventions for the Effective Health Care Program of the Agency for Healthcare Research and Quality: An Update Methods Guide for Effectiveness and Comparative Effectiveness Reviews. Rockville, MD 2013.
40 Ahmadizadeh MJ, Rezaei M. Unilateral right and bilateral dorsolateral prefrontal cortex transcranial magnetic stimulation in treatment post-traumatic stress disorder: A randomized controlled study. Brain Research Bulletin. 2018;140:334–340.29883597
41 Ahmed G, Maher EA, Elnassag Baemr Sayed HM, Kabbash SI. Effects of repetitive transcranial magnetic stimulation versus transcutaneous electrical nerve stimulation to decrease diabetic neuropathic pain. International journal of therapy & rehabilitation. 2020;27(2):1–10.
42 Altas EU, Askin A, Besiroglu L, Tosun A. Is high-frequency repetitive transcranial magnetic stimulation of the left primary motor cortex superior to the stimulation of the left dorsolateral prefrontal cortex in fibromyalgia syndrome? Somatosensory & Motor Research. 2019;36(1):56–62.30955403
43 Andre-Obadia N, Magnin M, Simon E, Garcia-Larrea L. Somatotopic effects of rTMS in neuropathic pain? A comparison between stimulation over hand and face motor areas. European Journal of Pain. 2018;22(4):707–715.29194849
44 Bilir B, Askin A, Sengul I, Tosun A. Effects of high frequency neuronavigated repetitive transcranial magnetic stimulation in fibromyalgia syndrome: A double-blinded, randomized controlled study. American Journal of Physical Medicine & Rehabilitation. 2020;20:20.
45 Cheng CM, Wang SJ, Su TP, . Analgesic effects of repetitive transcranial magnetic stimulation on modified 2010 criteria-diagnosed fibromyalgia: Pilot study. Psychiatry & Clinical Neurosciences. 2019;73(4):187–193.30588705
46 Choi GS, Kwak SG, Lee HD, Chang MC. Effect of high-frequency repetitive transcranial magnetic stimulation on chronic central pain after mild traumatic brain injury: A pilot study. Journal of Rehabilitation Medicine. 2018;50(3):246–252.29392332
47 Fryml LD, Pelic CG, Acierno R, . Exposure Therapy and Simultaneous Repetitive Transcranial Magnetic Stimulation: A Controlled Pilot Trial for the Treatment of Posttraumatic Stress Disorder. Journal of ECT. 2019;35(1):53–60.
48 Gaertner M, Kong JT, Scherrer KH, Foote A, Mackey S, Johnson KA. Advancing Transcranial Magnetic Stimulation Methods for Complex Regional Pain Syndrome: An Open-Label Study of Paired Theta Burst and High-Frequency Stimulation. Neuromodulation. 2018;21(4):409–416.29504190
49 Galhardoni R, Aparecida da Silva V, Garcia-Larrea L, . Insular and anterior cingulate cortex deep stimulation for central neuropathic pain: Disassembling the percept of pain. Neurology. 2019;92(18):e2165–e2175.30952795
50 Guinot M, Maindet C, Hodaj H, . Effects of repetitive transcranial magnetic stimulation and multicomponent therapy in patients with fibromyalgia: a randomized controlled trial. Arthritis care & research. 2019;30:30.
51 Hosomi K, Sugiyama K, Nakamura Y, . A randomized controlled trial of 5 daily sessions and continuous trial of 4 weekly sessions of repetitive transcranial magnetic stimulation for neuropathic pain. Pain. 2020;161(2):351–360.31593002
52 Hoy KE, McQueen S, Elliot D, Herring SE, Maller JJ, Fitzgerald PB. A Pilot Investigation of Repetitive Transcranial Magnetic Stimulation for Post-Traumatic Brain Injury Depression: Safety, Tolerability, and Efficacy. Journal of Neurotrauma. 2019;36(13):2092–2098.30712461
53 Isserles M, Shalev AY, Roth Y, . Effectiveness of deep transcranial magnetic stimulation combined with a brief exposure procedure in post-traumatic stress disorder--a pilot study. Brain Stimulation. 2013;6(3):377–383.22921765
54 Kim JK, Park HS, Bae JS, Jeong YS, Jung KJ, Lim JY. Effects of multi-session intermittent theta burst stimulation on central neuropathic pain: A randomized controlled trial. Neurorehabilitation. 2020;46(1):127–134.32039876
55 Kozel FA, Motes MA, Didehbani N, . Repetitive TMS to augment cognitive processing therapy in combat veterans of recent conflicts with PTSD: A randomized clinical trial. Journal of Affective Disorders. 2018;229:506–514.29351885
56 Kozel FA, Van Trees K, Larson V, . One hertz versus ten hertz repetitive TMS treatment of PTSD: A randomized clinical trial. Psychiatry Research. 2019;273:153–162.30641346
57 Lee SA, Kim MK. Effect of Low Frequency Repetitive Transcranial Magnetic Stimulation on Depression and Cognition of Patients with Traumatic Brain Injury: A Randomized Controlled Trial. Medical Science Monitor. 2018;24:8789–8794.30513530
58 Leong K, Chan P, Ong L, . A Randomized Sham-controlled Trial of 1-Hz and 10-Hz Repetitive Transcranial Magnetic Stimulation (rTMS) of the Right Dorsolateral Prefrontal Cortex in Civilian Post-traumatic Stress Disorder. Canadian Journal of Psychiatry - Revue Canadienne de Psychiatrie. 2020:706743720923064.
59 Leung A, Fallah A, Shukla S, . rTMS in Alleviating Mild TBI Related Headaches--A Case Series. Pain Physician. 2016;19(2):E347–354.26815263
60 Leung A, Metzger-Smith V, He Y, . Left Dorsolateral Prefrontal Cortex rTMS in Alleviating MTBI Related Headaches and Depressive Symptoms. Neuromodulation. 2018;21(4):390–401.28557049
61 Liu X, Zhao X, Liu T, . The effects of repetitive transcranial magnetic stimulation on cue-induced craving in male patients with heroin use disorder. EBioMedicine. 2020;56:102809.32512513
62 Manko G, Olszewski H, Krawczynski M, Tlokinski W. Evaluation of differentiated neurotherapy programs for patients recovering from severe TBI and long term coma. Acta Neuropsychologica. 2013;11(1):9–18.
63 Mattoo B, Tanwar S, Bhatia R, Tripathi M, Bhatia R. Repetitive transcranial magnetic stimulation in chronic tension-type headache: A pilot study. Indian Journal of Medical Research. 2019;150(1):73–80.
64 Nam DH, Pae CU, Chae JH. Low-frequency, Repetitive Transcranial Magnetic Stimulation for the Treatment of Patients with Posttraumatic Stress Disorder: a Double-blind, Sham-controlled Study. Clinical Psychopharmacology & Neuroscience. 2013;11(2):96–102.24023554
65 Petrosino NJ, Wout-Frank MV, Aiken E, . One-year clinical outcomes following theta burst stimulation for post-traumatic stress disorder. Neuropsychopharmacology. 2020;45(6):940–946.31794974
66 Philip NS, Aiken EE, Kelley ME, Burch W, Waterman L, Holtzheimer PE. Synchronized transcranial magnetic stimulation for posttraumatic stress disorder and comorbid major depression. Brain Stimulation. 2019;12(5):1335–1337.31204205
67 Philip NS, Barredo J, Aiken E, . Theta-Burst Transcranial Magnetic Stimulation for Posttraumatic Stress Disorder. American Journal of Psychiatry. 2019;176(11):939–948.
68 Quesada C, Pommier B, Fauchon C, . New procedure of high-frequency repetitive transcranial magnetic stimulation for central neuropathic pain: a placebo-controlled randomized crossover study. Pain. 2020;161(4):718–728.31764387
69 Rao V, Bechtold K, McCann U, . Low-Frequency Right Repetitive Transcranial Magnetic Stimulation for the Treatment of Depression After Traumatic Brain Injury: A Randomized Sham-Controlled Pilot Study. Journal of Neuropsychiatry & Clinical Neurosciences. 2019;31(4):306–318.
70 Sahu AK, Sinha VK, Goyal N. Effect of adjunctive intermittent theta-burst repetitive transcranial magnetic stimulation as a prophylactic treatment in migraine patients: A double-blind sham-controlled study. Indian Journal of Psychiatry. 2019;61(2):139–145.30992607
71 Shen Y, Cao X, Tan T, . 10-Hz Repetitive Transcranial Magnetic Stimulation of the Left Dorsolateral Prefrontal Cortex Reduces Heroin Cue Craving in Long-Term Addicts. Biological Psychiatry. 2016;80(3):e13–14.26995024
72 Shimizu T, Hosomi K, Maruo T, . Efficacy of deep rTMS for neuropathic pain in the lower limb: a randomized, double-blind crossover trial of an H-coil and figure-8 coil. Journal of Neurosurgery. 2017;127(5):1172–1180.28156250
73 Siddiqi S, Trapp N, Hacker C, . Repetitive Transcranial Magnetic Stimulation with Resting-State Network Targeting for Treatment-Resistant Depression in Traumatic Brain Injury: a Randomized, Controlled, Double-Blinded Pilot Study. Journal of neurotrauma. 2019;36(8):1361–1374.30381997
74 Stilling J, Paxman E, Mercier L, . Treatment of Persistent Post-Traumatic Headache and Post-Concussion Symptoms Using Repetitive Transcranial Magnetic Stimulation: A Pilot, Double-Blind, Randomized Controlled Trial. Journal of Neurotrauma. 2020;37(2):312–323.31530227
75 Watts BV, Landon B, Groft A, Young-Xu Y. A sham controlled study of repetitive transcranial magnetic stimulation for posttraumatic stress disorder. Brain Stimulation. 2012;5(1):38–43.22264669
76 Abd Elghany SE, Al Ashkar DS, El-Barbary AM, . Regenerative injection therapy and repetitive transcranial magnetic stimulation in primary fibromyalgia treatment: A comparative study. Journal of Back & Musculoskeletal Rehabilitation. 2019;32(1):55–62.30149440
77 Fitzgibbon BM, Hoy KE, Knox LA, . Evidence for the improvement of fatigue in fibromyalgia: A 4-week left dorsolateral prefrontal cortex repetitive transcranial magnetic stimulation randomized-controlled trial. European Journal of Pain. 2018;22(7):1255–1267.29542208
78 Neville IS, Zaninotto AL, Hayashi CY, . Repetitive TMS does not improve cognition in patients with TBI: A randomized double-blind trial. Neurology. 2019;93(2):e190–e199.31175209
79 Sun X, Long H, Zhao C, . Analgesia-enhancing effects of repetitive transcranial magnetic stimulation on neuropathic pain after spinal cord injury:An fNIRS study. Restorative Neurology & Neuroscience. 2019;37(5):497–507.31381538
80 Oznur T, Akarsu S, Celik C, . Is transcranial magnetic stimulation effective in treatment-resistant combat related posttraumatic stress disorder? Neurosciences. 2014;19(1):29–32.24419446
81 Koski L, Kolivakis T, Yu C, Chen JK, Delaney S, Ptito A. Noninvasive brain stimulation for persistent postconcussion symptoms in mild traumatic brain injury. Journal of Neurotrauma. 2015;32(1):38–44.24955920
82 Taghva A, Silvetz R, Ring A, . Magnetic Resonance Therapy Improves Clinical Phenotype and EEG Alpha Power in Posttraumatic Stress Disorder. Trauma Monthly. 2015;20(4):e27360.26839865
83 Leung A, Shukla S, Fallah A, . Repetitive Transcranial Magnetic Stimulation in Managing Mild Traumatic Brain Injury-Related Headaches. Neuromodulation. 2016;19(2):133–141.26555886
84 Philip NS, Ridout SJ, Albright SE, Sanchez G, Carpenter LL. 5-Hz Transcranial Magnetic Stimulation for Comorbid Posttraumatic Stress Disorder and Major Depression. Journal of Traumatic Stress. 2016;29(1):93–96.26748883
85 Seagly KS. PTSD symptom severity and neurocognitive performance as a function of combined TMS and imaginal exposure in OIF/OEF combat veterans with treatment resistant PTSD. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2016;77(3-B(E).
86 Woodside DB, Colton P, Lam E, Dunlop K, Rzeszutek J, Downar J. Dorsomedial prefrontal cortex repetitive transcranial magnetic stimulation treatment of posttraumatic stress disorder in eating disorders: An open-label case series. International Journal of Eating Disorders. 2017;50(10):1231–1234.
87 Carpenter LL, Conelea C, Tyrka AR, . 5Hz Repetitive transcranial magnetic stimulation for posttraumatic stress disorder comorbid with major depressive disorder. Journal of Affective Disorders. 2018;235:414–420.29677606
88 Lawson McLean A, Frank S, Zafar N, Waschke A, Kalff R, Reichart R. Time course of the response to navigated repetitive transcranial magnetic stimulation at 10 Hz in chronic neuropathic pain. Neurological Research. 2018;40(7):564–572.29583099
89 Quesada C, Pommier B, Fauchon C, . Robot-Guided Neuronavigated Repetitive Transcranial Magnetic Stimulation (rTMS) in Central Neuropathic Pain. Archives of Physical Medicine & Rehabilitation. 2018;99(11):2203–2215.e2201.29750900
90 Mrabet H, Mrabet A, Hattab N, Manai R, Zouari B. Repetitive transcranial magnetic stimulation as a treatment for chronic pain: A Tunisian series. Neurophysiologie Clinique. 2019;49(3):249–250.30711433
91 Pinot-Monange A, Moisset X, Chauvet P, . Repetitive Transcranial Magnetic Stimulation Therapy (rTMS) for Endometriosis Patients with Refractory Pelvic Chronic Pain: A Pilot Study. Journal of Clinical Medicine. 2019;8(4):13.
92 Hodaj H, Payen JF, Hodaj E, . Long-term treatment of chronic orofacial, pudendal, and central neuropathic limb pain with repetitive transcranial magnetic stimulation of the motor cortex. Clinical Neurophysiology. 2020;131(7):1423–1432.32387962
93 Nikkola J, Holm A, Seppanen M, Joutsi T, Rauhala E, Kaipia A. Repetitive Transcranial Magnetic Stimulation for Chronic Prostatitis/Chronic Pelvic Pain Syndrome: A Prospective Pilot Study. International neurourology journal. 2020;24(2):144–149.32615676
94 Nursey J, Sbisa A, Knight H, . Exploring Theta Burst Stimulation for Post-traumatic Stress Disorder in Australian Veterans-A Pilot Study. Military Medicine. 2020;30:30.
95 Liu H, Temel Y, Boonstra J, Hescham S. Correction to: The effect of fornix deep brain stimulation in brain diseases. Cellular & Molecular Life Sciences. 2020;14:14.
96 Gentry J, Bates E, Bidermann S, Jin Y, Zhang J. Magnetic E-Resonant Therapy Alleviates Combat Related Posttraumatic Stress Disorder.
97 Guerra A, Lopez-Alonso V, Cheeran B, Suppa A. Solutions for managing variability in non-invasive brain stimulation studies. Neuroscience Letters. 2020;719:133–332.
98 Lefaucheur J-P, Nguyen J-P. A practical algorithm for using rTMS to treat patients with chronic pain. Neurophysiologie Clinique. 2019;49(4):301–307.31375381

## Supplementary Materials

### APPENDIX A VA/DOD GUIDELINES

Year | Title | Condition | TMS-related guidance
2017 | Management of Posttraumatic Stress Disorder and Acute Stress Reaction 2017 | PTSD/Acute Stress Reaction | There is insufficient evidence to recommend for or against the following somatic therapies: repetitive transcranial magnetic stimulation (rTMS), electroconvulsive therapy (ECT), hyperbaric oxygen therapy (HBOT), stellate ganglion block (SGB), or vagal nerve stimulation (VNS).
2020 | The Primary Care Management of Headache | Headache | There is insufficient evidence to recommend for or against the following for headache:; - Transcranial magnetic stimulation; - Transcranial direct current stimulation; - External trigeminal nerve stimulation; - Supraorbital electrical stimulation
2016 | Management of Concussion-mild Traumatic Brain Injury (mTBI) | Concussion/mild Traumatic Brain Injury (mTBI) | There is no evidence to suggest for or against the use of any particular modality for the treatment (including rTMS) of tinnitus after mTBI.

### APPENDIX B SEARCHES

1. Search for current systematic reviews (limited to last 7 years); Date Searched: 08-06-2020
A. Bibliographic Databases: | # | Search Statement | Results:
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process & Other Non-Indexed Citations, Daily and Versions(R) 1946 to February 05, 2020 | 1 | Transcranial Magnetic Stimulation/ | 11013
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process & Other Non-Indexed Citations, Daily and Versions(R) 1946 to February 05, 2020 | 2 | (transcranial magnetic stimulation$1 or rTMS or TMS).mp. | 21201
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process & Other Non-Indexed Citations, Daily and Versions(R) 1946 to February 05, 2020 | 3 | 1 or 2 | 21201
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process & Other Non-Indexed Citations, Daily and Versions(R) 1946 to February 05, 2020 | 4 | (systematic review.ti. or meta-analysis.pt. or meta-analysis.ti. or systematic literature review.ti. or this systematic review.tw. or pooling project.tw. or (systematic review.ti,ab. and review.pt.) or meta synthesis.ti. or meta-analy*.ti. or integrative review.tw. or integrative research review.tw. or rapid review.tw. or umbrella review.tw. or consensus development conference.pt. or practice guideline.pt. or drug class reviews.ti. or cochrane database syst rev.jn. or acp journal club.jn. or health technol assess.jn. or evid rep technol assess summ.jn. or jbi database system rev implement rep.jn. or (clinical guideline and management).tw. or ((evidence based.ti. or evidence-based medicine/ or best practice*.ti. or evidence synthesis.ti,ab.) and (((review.pt. or diseases category/ or behavior.mp.) and behavior mechanisms/) or therapeutics/ or evaluation studies.pt. or validation studies.pt. or guideline.pt. or pmcbook.mp.)) or (((systematic or systematically).tw. or critical.ti,ab. or study selection.tw. or ((predetermined or inclusion) and criteri*).tw. or exclusion criteri*.tw. or main outcome measures.tw. or standard of care.tw. or standards of care.tw.) and ((survey or surveys).ti,ab. or overview*.tw. or review.ti,ab. or reviews.ti,ab. or search*.tw. or handsearch.tw. or analysis.ti. or critique.ti,ab. or appraisal.tw. or (reduction.tw. and (risk/ or risk.tw.) and (death or recurrence).mp.)) and ((literature or articles or publications or publication or bibliography or bibliographies or published).ti,ab. or pooled data.tw. or unpublished.tw. or citation.tw. or citations.tw. or database.ti,ab. or internet.ti,ab. or textbooks.ti,ab. or references.tw. or scales.tw. or papers.tw. or datasets.tw. or trials.ti,ab. or meta-analy*.tw. or (clinical and studies).ti,ab. or treatment outcome/ or treatment outcome.tw. or pmcbook.mp.))) not (letter or newspaper article).pt. | 382964
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process & Other Non-Indexed Citations, Daily and Versions(R) 1946 to February 05, 2020 | 5 | 3 and 4 | 717
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process & Other Non-Indexed Citations, Daily and Versions(R) 1946 to February 05, 2020 | 6 | limit 5 to english language | 686
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process & Other Non-Indexed Citations, Daily and Versions(R) 1946 to February 05, 2020 | 7 | limit 6 to last 7 years | 545
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 4, 2020 | 1 | Transcranial Magnetic Stimulation/ | 0
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 4, 2020 | 2 | (transcranial magnetic stimulation$1 or rTMS or TMS).mp. | 68
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 4, 2020 | 3 | 1 or 2 | 68
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 4, 2020 | 4 | limit 3 to last 7 years | 47

2. Search for systematic reviews currently under development (includes forthcoming reviews & protocols); Date Searched: 08-06-20
D. Under development: | Evidence: | Results:
PROSPERO (SR registry) | http://www.crd.york.ac.uk/PROSPERO/; Search: TMS; transcranial magnetic stimulation | 0
DoPHER (SR Protocols) | http://eppi.ioe.ac.uk/webdatabases4/Intro.aspx?ID=9; Search: TMS; transcranial magnetic stimulation | 0
Cochrane Database of Systematic Reviews: Protocols | http://www.ohsu.edu/xd/education/library/; See Cochrane search above | 0

3. Search for primary literature; Date searched: 08-15-20; MEDLINE [Ovid MEDLINE(R) ALL 1946 to July 14, 2020]
# | Search Statement | Results
1 | Transcranial Magnetic Stimulation/ | 11396
2 | (transcranial magnetic stimulation$1 or rTMS or TMS or (repetitive adj transcranial magnetic stimulation$1) or (single-pulse adj transcranial magnetic stimulation$1) or (paired?pulse adj transcranial magnetic stimulation$1)).ti,ab,kw. | 20349
3 | 1 or 2 | 21918
4 | Chronic Pain/ | 14451
5 | (chronic adj1 pain).ti,ab,kw. | 36934
6 | 4 or 5 | 43337
7 | 3 and 6 | 246
8 | limit 7 to english language | 236
9 | limit 8 to yr=”2017-Current” | 77
CINAHL [EBSCO]
# | Search Statement | Results
1 | (MH “Transcranial Magnetic Stimulation”) | 1234
2 | TI ( (transcranial magnetic stimulation# or rTMS or TMS or (repetitive N1 transcranial magnetic stimulation#) or (single-pulse N1 transcranial magnetic stimulation#) or (paired pulse N1 transcranial magnetic stimulation#)) ) OR AB ( (transcranial magnetic stimulation# or rTMS or TMS or (repetitive N1 transcranial magnetic stimulation#) or (single-pulse N1 transcranial magnetic stimulation#) or (paired?pulse N1 transcranial magnetic stimulation#)) ) | 3637
3 | 1 or 2 | 3896
4 | (MH “Chronic Pain”) | 23575
5 | TI (chronic N1 pain) OR AB (chronic N1 pain) | 27466
6 | 4 or 5 | 38370
7 | 3 and 6 | 118
8 | limit 7 to english language | 116
9 | limit 8 to 2017-Current | 30
CCRCT [EBM Reviews - Cochrane Central Register of Controlled Trials June 2020]
# | Search Statement | Results
1 | Transcranial Magnetic Stimulation/ | 1360
2 | (transcranial magnetic stimulation$1 or rTMS or TMS or (repetitive adj transcranial magnetic stimulation$1) or (single-pulse adj transcranial magnetic stimulation$1) or (paired?pulse adj transcranial magnetic stimulation$1)).ti,ab,kw. | 5643
3 | 1 or 2 | 5823
4 | Chronic Pain/ | 2241
5 | (chronic adj1 pain).ti,ab,kw. | 8487
6 | 4 or 5 | 9437
7 | 3 and 6 | 139
8 | limit 7 to english language | 90
9 | limit 8 to yr=”2017-Current” | 37

4. Search for primary literature - TMS-all + PTSD/TBI/Opioid addiction/MST; Date searched: 08-10-20
MEDLINE [Ovid MEDLINE(R) ALL 1946 to August 07, 2020]
# | Search Statement | Results
1 | exp Transcranial Magnetic Stimulation/ or Magnetic Stimulation Therapy/ | 12590
2 | (TMS or ((transcrani* or crani* or brain*) adj4 (electrostim* or electro-stim* or electrotherap* or electro-therap*)) or electrical stimulation or electrical treatment or ((brain* or cortex or cortical or transcranial* or cranial or magneti*) adj4 stimulat*) or (transcranial magnetic stimulation or rTMS or cranial electrostimulation or cranial electrotherapy)).ti,ab,kw. | 95929
3 | (MeRT or magnetic eResonance therapy or magnetic e-Resonance therapy).ti,ab,kw. | 268
4 | (magnetic EEG?EKG guidance resonance therapy or magnetic EEG guided resonance therapy or magnetic EEG-guided resonance therapy or magnetic EKG-guided resonance therapy or magnetic EKG-guided resonance therapy).ti,ab,kw. | 0
5 | (EEG?EKG guided TMS or EEG guided TMS or EEG-guided TMS or EKG guided TMS or EKG-guided TMS or EEG guided transcranial magnetic stimulation or EEG-guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or q-EEG or quantitative EEG).ti,ab,kw. | 1402
6 | or/1-5 | 99318
7 | Stress Disorders, Post-Traumatic/ or exp Brain Injuries, Traumatic/ or exp Opioid-Related Disorders/ or Sexual Harassment/ or exp Sex Offenses/ | 96630
8 | (PTSD or post-traumatic stress disorder or posttraumatic stress disorder or post-traumatic stress disorders or posttraumatic stress disorders or post-traumatic neuroses or posttraumatic neuroses or moral injury or moral injuries).ti,ab,kw. | 34503
9 | (TBI or TBIs or traumatic brain injury or traumatic brain injuries or brain trauma or brain traumas or traumatic encephalopathy or traumatic encephalopathies).ti,ab,kw. | 44065
10 | (opioid related disorders or opioid-related disorders or opioid addiction or opioid addictions or opioid dependence or opioid dependences or opiate abuse or opiate abuses or opiate dependence or opiate addiction or opioid abuse or opioid abuses).ti,ab,kw. | 7202
11 | ((sexual* adj1 (trauma or abuse or violence or harassment or assault or assults or assulted) or (sex* adj1 offense or offenses) or rape or raped)).ti,ab,kw. | 30052
12 | or/7-11 | 160123
13 | 6 and 12 | 802
14 | limit 13 to english language | 770
15 | limit 14 to yr=”2012-Current” | 541
CINAHL [EBSCO]
# | Search Statement | Results
1 | (MH “Transcranial Magnetic Stimulation”) | 1215
2 | TI ( (TMS or ((transcrani* or crani* or brain*) adj4 (electrostim* or electro-stim* or electrotherap* or electro-therap*)) or electrical stimulation or electrical treatment or ((brain* or cortex or cortical or transcranial* or cranial or magneti*) adj4 stimulat*) or (transcranial magnetic stimulation or rTMS or cranial electrostimulation or cranial electrotherapy)) ) OR AB ((TMS or ((transcrani* or crani* or brain*) adj4 (electrostim* or electro-stim* or electrotherap* or electro-therap*)) or electrical stimulation or electrical treatment or ((brain* or cortex or cortical or transcranial* or cranial or magneti*) adj4 stimulat*) or (transcranial magnetic stimulation or rTMS or cranial electrostimulation or cranial electrotherapy)) ) OR SU ((TMS or ((transcrani* or crani* or brain*) adj4 (electrostim* or electro-stim* or electrotherap* or electro-therap*)) or electrical stimulation or electrical treatment or ((brain* or cortex or cortical or transcranial* or cranial or magneti*) adj4 stimulat*) or (transcranial magnetic stimulation or rTMS or cranial electrostimulation or cranial electrotherapy)) ) | 10359
3 | TI ( (MeRT or magnetic eResonance therapy or magnetic e-Resonance therapy) ) OR AB ( (MeRT or magnetic eResonance therapy or magnetic e-Resonance therapy) ) OR SU ( (MeRT or magnetic eResonance therapy or magnetic e-Resonance therapy) ) | 40
4 | TI ( (magnetic EEG?EKG guidance resonance therapy or magnetic EEG guided resonance therapy or magnetic EEG-guided resonance therapy or magnetic EKG-guided resonance therapy or magnetic EKG-guided resonance therapy) ) OR AB ( (magnetic EEG?EKG guidance resonance therapy or magnetic EEG guided resonance therapy or magnetic EEG-guided resonance therapy or magnetic EKG-guided resonance therapy or magnetic EKG-guided resonance therapy) ) OR SU ( (magnetic EEG?EKG guidance resonance therapy or magnetic EEG guided resonance therapy or magnetic EEG-guided resonance therapy or magnetic EKG-guided resonance therapy or magnetic EKG-guided resonance therapy) ) | 0
5 | TI ( (EEG?EKG guided TMS or EEG guided TMS or EEG-guided TMS or EKG guided TMS or EKG-guided TMS or EEG guided transcranial magnetic stimulation or EEG-guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or q-EEG or quantitative EEG) ) OR AB ( (EEG?EKG guided TMS or EEG guided TMS or EEG-guided TMS or EKG guided TMS or EKG-guided TMS or EEG guided transcranial magnetic stimulation or EEG-guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or q-EEG or quantitative EEG) ) OR SU ( (EEG?EKG guided TMS or EEG guided TMS or EEG-guided TMS or EKG guided TMS or EKG-guided TMS or EEG guided transcranial magnetic stimulation or EEG-guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or q-EEG or quantitative EEG) ) | 226
6 | S1 OR S2 OR S3 OR S4 OR S5 | 10622
7 | (MH “Stress Disorders, Post-Traumatic+”) OR (MH “Brain Injuries+”) OR (MH “Sexual Harassment”) OR (MH “Substance Use Disorders+”) | 214680
8 | TI ( (PTSD or post-traumatic stress disorder or posttraumatic stress disorder or post-traumatic stress disorders or posttraumatic stress disorders or post-traumatic neuroses or posttraumatic neuroses or moral injury or moral injuries) ) OR AB ( (PTSD or post-traumatic stress disorder or posttraumatic stress disorder or post-traumatic stress disorders or posttraumatic stress disorders or post-traumatic neuroses or posttraumatic neuroses or moral injury or moral injuries) ) OR SU ( (PTSD or post-traumatic stress disorder or posttraumatic stress disorder or post-traumatic stress disorders or posttraumatic stress disorders or post-traumatic neuroses or posttraumatic neuroses or moral injury or moral injuries) ) | 16203
9 | TI ( (TBI or TBIs or traumatic brain injury or traumatic brain injuries or brain trauma or brain traumas or traumatic encephalopathy or traumatic encephalopathies) ) OR AB ( (TBI or TBIs or traumatic brain injury or traumatic brain injuries or brain trauma or brain traumas or traumatic encephalopathy or traumatic encephalopathies) ) OR SU ( (TBI or TBIs or traumatic brain injury or traumatic brain injuries or brain trauma or brain traumas or traumatic encephalopathy or traumatic encephalopathies) ) | 17087
10 | TI ( (opioid related disorders or opioid-related disorders or opioid addiction or opioid addictions or opioid dependence or opioid dependences or opiate abuse or opiate abuses or opiate dependence or opiate addiction or opioid abuse or opioid abuses) ) OR AB ( (opioid related disorders or opioid-related disorders or opioid addiction or opioid addictions or opioid dependence or opioid dependences or opiate abuse or opiate abuses or opiate dependence or opiate addiction or opioid abuse or opioid abuses) ) OR SU ( (opioid related disorders or opioid-related disorders or opioid addiction or opioid addictions or opioid dependence or opioid dependences or opiate abuse or opiate abuses or opiate dependence or opiate addiction or opioid abuse or opioid abuses) ) | 3476
11 | TI ( ((sexual* adj1 (trauma or abuse or violence or harassment or assault or assults or assulted) or (sex* adj1 offense or offenses) or rape or raped)) ) OR AB ( ((sexual* adj1 (trauma or abuse or violence or harassment or assault or assults or assulted) or (sex* adj1 offense or offenses) or rape or raped)) ) OR SU ( ((sexual* adj1 (trauma or abuse or violence or harassment or assault or assults or assulted) or (sex* adj1 offense or offenses) or rape or raped)) ) | 6905
12 | S7 or S8 or S9 or S10 or S11 | 228968
13 | S6 and S12 | 283
14 | limit 13 to english language | 282
15 | limit 14 to yr=”2012-Current” | 191
CCRCT [EBM Reviews - Cochrane Central Register of Controlled Trials July 2020]
# | Search Statement | Results
1 | exp Transcranial Magnetic Stimulation/ or Magnetic Stimulation Therapy/ | 1537
2 | (TMS or ((transcrani* or crani* or brain*) adj4 (electrostim* or electro-stim* or electrotherap* or electro-therap*)) or electrical stimulation or electrical treatment or ((brain* or cortex or cortical or transcranial* or cranial or magneti*) adj4 stimulat*) or (transcranial magnetic stimulation or rTMS or cranial electrostimulation or cranial electrotherapy)).ti,ab,kw. | 17132
3 | (MeRT or magnetic eResonance therapy or magnetic e-Resonance therapy).ti,ab,kw. | 8
4 | (magnetic EEG?EKG guidance resonance therapy or magnetic EEG guided resonance therapy or magnetic EEG-guided resonance therapy or magnetic EKG-guided resonance therapy or magnetic EKG-guided resonance therapy).ti,ab,kw. | 0
5 | (EEG?EKG guided TMS or EEG guided TMS or EEG-guided TMS or EKG guided TMS or EKG-guided TMS or EEG guided transcranial magnetic stimulation or EEG-guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or q-EEG or quantitative EEG).ti,ab,kw. | 309
6 | or/1-5 | 17606
7 | Stress Disorders, Post-Traumatic/ or exp Brain Injuries, Traumatic/ or exp Opioid-Related Disorders/ or Sexual Harassment/ or exp Sex Offenses/ | 6821
8 | (PTSD or post-traumatic stress disorder or posttraumatic stress disorder or post-traumatic stress disorders or posttraumatic stress disorders or post-traumatic neuroses or posttraumatic neuroses or moral injury or moral injuries).ti,ab,kw. | 5644
9 | (TBI or TBIs or traumatic brain injury or traumatic brain injuries or brain trauma or brain traumas or traumatic encephalopathy or traumatic encephalopathies).ti,ab,kw. | 4539
10 | (opioid related disorders or opioid-related disorders or opioid addiction or opioid addictions or opioid dependence or opioid dependences or opiate abuse or opiate abuses or opiate dependence or opiate addiction or opioid abuse or opioid abuses).ti,ab,kw. | 2061
11 | (sexual* trauma or sexual* abuse or sexual* violence or sex* offense or sex* offenses or sexual* harassment or sexual* assault or sexual* assaults or sexual* assaulted or rape or raped).ti,ab,kw. | 1531
12 | or/7-11 | 15898
13 | 6 and 12 | 418
14 | limit 13 to english language | 230
15 | limit 14 to yr=”2012-Current” | 202
PsycINFO [Ovid, APA PsycInfo 1806 to August Wk 1 2020]
# | Search Statement | Results
1 | exp Transcranial Magnetic Stimulation/ | 8425
2 | (TMS or ((transcrani* or crani* or brain*) adj4 (electrostim* or electro-stim* or electrotherap* or electro-therap*)) or electrical stimulation or electrical treatment or ((brain* or cortex or cortical or transcranial* or cranial or magneti*) adj4 stimulat*) or (transcranial magnetic stimulation or rTMS or cranial electrostimulation or cranial electrotherapy)).ti,ab,id. | 31753
3 | (MeRT or magnetic eResonance therapy or magnetic e-Resonance therapy).ti,ab,id. | 25
4 | (magnetic EEG?EKG guidance resonance therapy or magnetic EEG guided resonance therapy or magnetic EEG-guided resonance therapy or magnetic EKG-guided resonance therapy or magnetic EKG-guided resonance therapy).ti,ab,id. | 0
5 | (EEG?EKG guided TMS or EEG guided TMS or EEG-guided TMS or EKG guided TMS or EKG-guided TMS or EEG guided transcranial magnetic stimulation or EEG-guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or q-EEG or quantitative EEG).ti,ab,id. | 848
6 | or/1-5 | 32760
7 | exp Posttraumatic Stress Disorder/ or exp Traumatic Brain Injury/ or exp “Opioid Use Disorder”/ or exp Sexual Harassment/ or exp Sex Offenses/ | 92255
8 | (PTSD or post-traumatic stress disorder or posttraumatic stress disorder or post-traumatic stress disorders or posttraumatic stress disorders or post-traumatic neuroses or posttraumatic neuroses or moral injury or moral injuries).ti,ab,id. | 42280
9 | (TBI or TBIs or traumatic brain injury or traumatic brain injuries or brain trauma or brain traumas or traumatic encephalopathy or traumatic encephalopathies).ti,ab,id. | 18909
10 | (opioid related disorders or opioid-related disorders or opioid addiction or opioid addictions or opioid dependence or opioid dependences or opiate abuse or opiate abuses or opiate dependence or opiate addiction or opioid abuse or opioid abuses).ti,ab,id. | 4358
11 | (sexual* trauma or sexual* abuse or sexual* violence or sex* offense or sex* offenses or sexual* harassment or sexual* assault or sexual* assaults or sexual* assaulted or rape or raped).ti,ab,id. | 42333
12 | or/7-12 | 122224
13 | 6 and 12 | 488
14 | limit 13 to english language | 468
15 | limit 14 to yr=”2012-Current” | 314

5. Search for primary literature - TMS-all + Chronic pain-post2017; Date searched: 08-10-20
MEDLINE [Ovid MEDLINE(R) ALL 1946 to August 06, 2020]
# | Search Statement | Results
1 | exp Transcranial Magnetic Stimulation/ or Magnetic Stimulation Therapy/ | 12590
2 | (TMS or ((transcrani* or crani* or brain*) adj4 (electrostim* or electro-stim* or electrotherap* or electro-therap*)) or electrical stimulation or electrical treatment or ((brain* or cortex or cortical or transcranial* or cranial or magneti*) adj4 stimulat*) or (transcranial magnetic stimulation or rTMS or cranial electrostimulation or cranial electrotherapy)).ti,ab,kw. | 95929
3 | (MeRT or magnetic eResonance therapy or magnetic e-Resonance therapy).ti,ab,kw. | 268
4 | (magnetic EEG?EKG guidance resonance therapy or magnetic EEG guided resonance therapy or magnetic EEG-guided resonance therapy or magnetic EKG-guided resonance therapy or magnetic EKG-guided resonance therapy).ti,ab,kw. | 0
5 | (EEG?EKG guided TMS or EEG guided TMS or EEG-guided TMS or EKG guided TMS or EKG-guided TMS or EEG guided transcranial magnetic stimulation or EEG-guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or q-EEG or quantitative EEG).ti,ab,kw. | 1402
6 | or/1-5 | 99318
7 | Chronic Pain/ | 14595
8 | ((chronic* or back or musculoskel* or intractabl* or neuropath* or phantom limb or fantom limb or neck or myofasc* or “temporomandib* joint*” or “temperomandib* joint*” or “tempromandib* joint*” or central or post*stroke or complex or regional or spinal cord) adj4 pain*) or (sciatica or back-ache or back*ache or lumbago or fibromyalg* or (trigemin* adj2 neuralg*) or (herp* adj2 neuralg*) or (diabet* adj2 neuropath*) or (reflex adj4 dystroph*) or (sudeck* adj2 atroph*) or causalg* or whip-lash or whip*lash or polymyalg* or (failed back adj4 surg*) or (failed back adj4 syndrome*)).ti,ab,kw. | 207706
9 | 7 or 8 | 207706
10 | 6 and 9 | 2887
11 | limit 10 to english language | 2719
12 | limit 11 to yr=”2017-current” | 674
CINAHL [EBSCO]
# | Search Statement | Results
1 | (MH “Transcranial Magnetic Stimulation”) | 1215
2 | TI ( (TMS or ((transcrani* or crani* or brain*) adj4 (electrostim* or electro-stim* or electrotherap* or electro-therap*)) or electrical stimulation or electrical treatment or ((brain* or cortex or cortical or transcranial* or cranial or magneti*) adj4 stimulat*) or (transcranial magnetic stimulation or rTMS or cranial electrostimulation or cranial; electrotherapy)) ) OR AB ((TMS or ((transcrani* or crani* or brain*) adj4 (electrostim* or electro-stim* or electrotherap* or electro-therap*)) or electrical stimulation or electrical treatment or ((brain* or cortex or cortical or transcranial* or cranial or magneti*) adj4 stimulat*) or (transcranial magnetic stimulation or rTMS or cranial electrostimulation or cranial electrotherapy)) ) OR SU ((TMS or ((transcrani* or crani* or brain*) adj4 (electrostim* or electro-stim* or electrotherap* or electro-therap*)) or electrical stimulation or electrical treatment or ((brain* or cortex or cortical or transcranial* or cranial or magneti*) adj4 stimulat*) or (transcranial magnetic stimulation or rTMS or cranial electrostimulation or cranial electrotherapy)) ) | 10359
3 | TI ( (MeRT or magnetic eResonance therapy or magnetic e-Resonance therapy) ) OR AB ( (MeRT or magnetic eResonance therapy or magnetic e-Resonance therapy) ) OR SU ( (MeRT or magnetic eResonance therapy or magnetic e-Resonance therapy) ) | 40
4 | TI ( (magnetic EEG?EKG guidance resonance therapy or magnetic EEG guided resonance therapy or magnetic EEG-guided resonance therapy or magnetic EKG-guided resonance therapy or magnetic EKG-guided resonance therapy) ) OR AB ( (magnetic EEG?EKG guidance resonance therapy or magnetic EEG guided resonance therapy or magnetic EEG-guided resonance therapy or magnetic EKG-guided resonance therapy or magnetic EKG-guided resonance therapy) ) OR SU ( (magnetic EEG?EKG guidance resonance therapy or magnetic EEG guided resonance therapy or magnetic EEG-guided resonance therapy or magnetic EKG-guided resonance therapy or magnetic EKG-guided resonance therapy) ) | 0
5 | TI ( (EEG?EKG guided TMS or EEG guided TMS or EEG-guided TMS or EKG guided TMS or EKG-guided TMS or EEG guided transcranial magnetic stimulation or EEG-guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or q-EEG or quantitative EEG) ) OR AB ( (EEG?EKG guided TMS or EEG guided TMS or EEG-guided TMS or EKG guided TMS or EKG-guided TMS or EEG guided transcranial magnetic stimulation or EEG-guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or q-EEG or quantitative EEG) ) OR SU ( (EEG?EKG guided TMS or EEG guided TMS or EEG-guided TMS or EKG guided TMS or EKG-guided TMS or EEG guided transcranial magnetic stimulation or EEG-guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or q-EEG or quantitative EEG) ) | 226
6 | S1 OR S2 OR S3 OR S4 OR S5 | 10622
7 | (MH “Chronic Pain”) | 12958
8 | TI ( ((chronic* or back or musculoskel* or intractabl* or neuropath* or phantom limb or fantom limb or neck or myofasc* or “temporomandib* joint*” or “temperomandib* joint*” or “tempromandib* joint*” or central or post*stroke or complex or regional or spinal cord) adj4 pain*) or (sciatica or back-ache or back*ache or lumbago or fibromyalg* or (trigemin* adj2 neuralg*) or (herp* adj2 neuralg*) or (diabet* adj2 neuropath*) or (reflex adj4 dystroph*) or (sudeck* adj2 atroph*) or causalg* or whip-lash or whip*lash or polymyalg* or (failed back adj4 surg*) or (failed back adj4 syndrome*)) ) OR AB ( ((chronic* or back or musculoskel* or intractabl* or neuropath* or phantom limb or fantom limb or neck or myofasc* or “temporomandib* joint*” or “temperomandib* joint*” or “tempromandib* joint*” or central or post*stroke or complex or regional or spinal cord) adj4 pain*) or (sciatica or back-ache or back*ache or lumbago or fibromyalg* or (trigemin* adj2 neuralg*) or (herp* adj2 neuralg*) or (diabet* adj2 neuropath*) or (reflex adj4 dystroph*) or (sudeck* adj2 atroph*) or causalg* or whip-lash or whip*lash or polymyalg* or (failed back adj4 surg*) or (failed back adj4 syndrome*)) ) OR SU ( ((chronic* or back or musculoskel* or intractabl* or neuropath* or phantom limb or fantom limb or neck or myofasc* or “temporomandib* joint*” or “temperomandib* joint*” or “tempromandib* joint*” or central or post*stroke or complex or regional or spinal cord) adj4 pain*) or (sciatica or back-ache or back*ache or lumbago or fibromyalg* or (trigemin* adj2 neuralg*) or (herp* adj2 neuralg*) or (diabet* adj2 neuropath*) or (reflex adj4 dystroph*) or (sudeck* adj2 atroph*) or causalg* or whip-lash or whip*lash or polymyalg* or (failed back adj4 surg*) or (failed back adj4 syndrome*)) ) | 5599
9 | S7 or S8 | 18008
10 | S6 and S9 | 136
11 | limit 10 to english language | 136
12 | limit 11 to yr=”2017-current” | 52
CCRCT [EBM Reviews - Cochrane Central Register of Controlled Trials July 2020]
# | Search Statement | Results
1 | exp Transcranial Magnetic Stimulation/ or Magnetic Stimulation Therapy/ | 1537
2 | (TMS or ((transcrani* or crani* or brain*) adj4 (electrostim* or electro-stim* or electrotherap* or electro-therap*)) or electrical stimulation or electrical treatment or ((brain* or cortex or cortical or transcranial* or cranial or magneti*) adj4 stimulat*) or (transcranial magnetic stimulation or rTMS or cranial electrostimulation or cranial electrotherapy)).ti,ab,kw. | 17132
3 | (MeRT or magnetic eResonance therapy or magnetic e-Resonance therapy).ti,ab,kw. | 8
4 | (magnetic EEG/EKG guidance resonance therapy or magnetic EEG guided resonance therapy or magnetic EEG-guided resonance therapy or magnetic EKG-guided resonance therapy or magnetic EKG-guided resonance therapy).ti,ab,kw. | 0
5 | (EEG?EKG guided TMS or EEG guided TMS or EEG-guided TMS or EKG guided TMS or EKG-guided TMS or EEG guided transcranial magnetic stimulation or EEG-guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or q-EEG or quantitative EEG).ti,ab,kw. | 309
6 | or/1-5 | 17606
7 | Chronic Pain/ | 2274
8 | ((chronic* or back or musculoskel* or intractabl* or neuropath* or phantom limb or fantom limb or neck or myofasc* or “temporomandib* joint*” or “temperomandib* joint*” or “tempromandib* joint*” or central or post*stroke or complex or regional or spinal cord) adj4 pain*) or (sciatica or back-ache or back*ache or lumbago or fibromyalg* or (trigemin* adj2 neuralg*) or (herp* adj2 neuralg*) or (diabet* adj2 neuropath*) or (reflex adj4 dystroph*) or (sudeck* adj2 atroph*) or causalg* or whip-lash or whip*lash or polymyalg* or (failed back adj4 surg*) or (failed back adj4 syndrome*)).ti,ab,kw. | 45397
9 | 7 or 8 | 45397
10 | 6 and 9 | 1342
11 | limit 10 to english language | 806
12 | limit 11 to yr=”2017-current” | 307
PsycINFO [Ovid, APA PsycInfo 1806 to August Wk 1 2020]
# | Search Statement | Results
1 | exp Transcranial Magnetic Stimulation/ | 8425
2 | (TMS or ((transcrani* or crani* or brain*) adj4 (electrostim* or electro-stim* or electrotherap* or electro-therap*)) or electrical stimulation or electrical treatment or ((brain* or cortex or cortical or transcranial* or cranial or magneti*) adj4 stimulat*) or (transcranial magnetic stimulation or rTMS or cranial electrostimulation or cranial electrotherapy)).ti,ab,id. | 31753
3 | (MeRT or magnetic eResonance therapy or magnetic e-Resonance therapy).ti,ab,kw. | 25
4 | (magnetic EEG/EKG guidance resonance therapy or magnetic EEG guided resonance therapy or magnetic EEG-guided resonance therapy or magnetic EKG-guided resonance therapy or magnetic EKG-guided resonance therapy).ti,ab,id. | 0
5 | (EEG?EKG guided TMS or EEG guided TMS or EEG-guided TMS or EKG guided TMS or EKG-guided TMS or EEG guided transcranial magnetic stimulation or EEG-guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or EKG guided transcranial magnetic stimulation or q-EEG or quantitative EEG).ti,ab,id. | 848
6 | or/1-5 | 32760
7 | exp Chronic Pain/ | 13491
8 | (((chronic* or back or musculoskel* or intractabl* or neuropath* or phantom limb or fantom limb or neck or myofasc* or “temporomandib* joint*” or “temperomandib* joint*” or “tempromandib* joint*” or central or post*stroke or complex or regional or spinal cord) adj4 pain*) or (sciatica or back-ache or back*ache or lumbago or fibromyalg* or (trigemin* adj2 neuralg*) or (herp* adj2 neuralg*) or (diabet* adj2 neuropath*) or (reflex adj4 dystroph*) or (sudeck* adj2 atroph*) or causalg* or whip-lash or whip*lash or polymyalg* or (failed back adj4 surg*) or (failed back adj4 syndrome*))).ti,ab,id. | 35688
9 | 7 or 8 | 36491
10 | 6 and 9 | 861
11 | limit 10 to english language | 821
12 | limit 11 to yr=”2017-Current” | 157

6. ClinicalTrials.gov^*^; Date Searched: 08-27-20
# | Search Statement | Results
1 | Condition or disease: PTSD or post-traumatic stress disorder or posttraumatic stress disorder or traumatic brain injury or TBI or opioid or opioids or sexual trauma or sexual abuse or sexual violence or chronic pain; Other terms: TMS or transcranial magnetic stimulation or MeRT or magnetic eResonance therapy or magnetic EEG/EKG guidance resonance therapy EEG guidance or EKG guidance or magnetic stimulation therapy | 0
2 | Condition or disease: PTSD or post-traumatic stress disorder or posttraumatic stress disorder; Other terms: TMS or transcranial magnetic stimulation | 26
3 | Condition or disease: PTSD or post-traumatic stress disorder or posttraumatic stress disorder; Other terms: MeRT | 2
4 | Condition or disease: traumatic brain injury or TBI or concussion; Other terms: TMS or transcranial magnetic stimulation | 3
5 | Condition or disease: traumatic brain injury or TBI or concussion; Other terms: MeRT | 1
6 | Condition or disease: opioid or opioids; Other terms: TMS or transcranial magnetic stimulation | 12
8 | Condition or disease: chronic pain; Other terms: TMS or transcranial magnetic stimulation | 42

* No results for: sexual trauma and any intervention; EEG/EKG-guided resonance therapy and any condition; MeRT and opioid addiction, chronic pain

### APPENDIX C EXCLUDED STUDIES

Exclude reasons: 1=Ineligible population, 2=Ineligible intervention, 3=Ineligible comparator, 4=Ineligible outcome, 5=Ineligible timing, 6=Ineligible study design, 7=Ineligible publication type 8=Outdated or ineligible systematic review, 9=Non-prioritized pain area, 10=Unable to locate full-text

# | Citation | Exclude Reason
1 | Aamir, A., . (2020). “Repetitive Magnetic Stimulation for the Management of Peripheral Neuropathic Pain: A Systematic Review.” [underlined: Advances in Therapy] 37(3): 998–1012.31989485 31989485 | E7
2 | Adamson, M., . (2020). “Repetitive transcranial magnetic stimulation for improving cognition in veterans with TBI: results from pilot clinical trial.” [underlined: Brain Stimulation] 12(2): 551-. | E4
3 | Adamson, M., . (2020). “Repetitive transcranial magnetic stimulation for improving cognition in veterans with TBI: results from pilot clinical trial.” [underlined: Brain Stimulation] 12(2): 551-. | E6
4 | Ansado, J., . (2019). “Impact of non-invasive brain stimulation on transcallosal modulation in mild traumatic brain injury: a multimodal pilot investigation.” Brain Injury 33(8): 1021–1031.31170014 | E4
5 | Akyuz, G. and E. Giray (2019). “Noninvasive neuromodulation techniques for the management of phantom limb pain: a systematic review of randomized controlled trials.” [underlined: International Journal of Rehabilitation Research] 42(1): 1–10.30222617 | E7
6 | Baptista, A. F., . (2019). “Latin American and Caribbean consensus on noninvasive central nervous system neuromodulation for chronic pain management (LAC<sub>2</sub>-NIN-CP).” [underlined: The Pain Report] 4(1): e692. | E7
7 | Berlim, M. T. and F. Van Den Eynde (2014). “Repetitive transcranial magnetic stimulation over the dorsolateral prefrontal cortex for treating posttraumatic stress disorder: an exploratory meta-analysis of randomized, double-blind and sham-controlled trials.” [underlined: Canadian Journal of Psychiatry - Revue Canadienne de Psychiatrie] 59(9): 487–496.25565694 | E7
8 | Berlim, M. T. and F. Van Den Eynde (2014). “Repetitive transcranial magnetic stimulation over the dorsolateral prefrontal cortex for treating posttraumatic stress disorder: an exploratory meta-analysis of randomized, double-blind and sham-controlled trials.” [underlined: Canadian Journal of Psychiatry - Revue Canadienne de Psychiatrie] 59(9): 487–496.25565694 | E7
9 | Bhatia, R., . (2017). “Transcranial magnetic stimulation of dorsolateral prefrontal cortex in chronic pain management.” [underlined: Brain Stimulation] 10(2): 434–435. | E6
10 | Blanchard, D. and S. Bourgeois (2017). “Efficacy of non-invasive brain stimulation for people experiencing chronic pain.” [underlined: International Journal of Evidence-Based Healthcare] 15(2): 79–80.28520573 | E6
11 | Bogdanova, Y., . (2015). “Sleep problems, treatment and recovery in veterans with blast exposure, TBI and PTSD.” [underlined: Archives of physical medicine and rehabilitation] 96(10): e3–e4. | E6
12 | Bursali, C., . (2019). “Effectiveness of repetitive transcranial magnetic stimulation in patients with failed back surgery syndrome.” [underlined: Annals of the rheumatic diseases] 78. | E6
13 | Castel-Lacanal, E., . (2014). “Transcranial magnetic stimulation in brain injury.” [underlined: Annales Francaises d Anesthesie et de Reanimation] 33(2): 83–87.24378049 | E7
14 | Cervigni, M., . (2018). “Repetitive transcranial magnetic stimulation for chronic neuropathic pain in patients with bladder pain syndrome/interstitial cystitis.” [underlined: Neurourology & Urodynamics] 37(8): 2678–2687.29797500 | E9
15 | Chan, P., . (2019). “The Role of Fast or Slow Repetitive Transcranial Magnetic Stimulation in Civilian Post-Traumatic Stress Disorder: a Randomized, Sham-Controlled Trial.” [underlined: Brain Stimulation] 12(4): e132-. | E6
16 | Choi, G. S., . (2018). “Effect of high-frequency repetitive transcranial magnetic stimulation on chronic central pain after mild traumatic brain injury: A pilot study.” [underlined: Journal of Rehabilitation Medicine] 50(3): 246–252 29392332 | E9
17 | Cirillo, P., . (2019). “Transcranial magnetic stimulation in anxiety and trauma-related disorders: A systematic review and meta-analysis.” [underlined: Brain and Behavior] 9(6): e01284.31066227 | E7
18 | Cogne, M., . (2017). “Seizure induced by repetitive transcranial magnetic stimulation for central pain: Adapted guidelines for post-stroke patients.” [underlined: Brain Stimulation] 10(4): 862–864.28359831 | E6
19 | Cohen, B., . (2017). “Deep tms augmentation treatment for fibromyalgia: a safety and feasibility study.” [underlined: Brain stimulation. Conference: 2nd international brain stimulation conference. Spain] 10(2): 450. | E6
20 | Coles, A., . (2018). “A review of brain stimulation methods to treat substance use disorders.” [underlined: American Journal on Addictions] 27(2): 71–91 | E2
21 | Cordero-Gessa, A. and L. Espejo-Antúnez (2019). “Eficacia de la estimulación magnética transcraneal de baja intensidad en mujeres diagnosticadas de fibromialgia. Un estudio piloto.” [underlined: Fisioterapia] 41(2): 99–106. | E8
22 | Etoh, S. (2017). “Effect of the repetitive transcranial magnetic stimulation and motor imagery therapy on the central pain after stroke.” | E10
23 | Dhaliwal, S. K., . (2015). “Non-Invasive Brain Stimulation for the Treatment of Symptoms Following Traumatic Brain Injury.” [underlined: Frontiers in psychiatry Frontiers Research Foundation] 6: 119.
24 | Ferreira, N. R., . (2019). “The efficacy of transcranial direct current stimulation and transcranial magnetic stimulation for chronic orofacial pain: A systematic review.” [underlined: PLoS ONE [Electronic Resource]] 14(8): e0221110. | E7
25 | Ferrulli, A., . (2019). “Deep transcranial magnetic stimulation in patients with obesity: italian safety data.” [underlined: Obesity facts] 12(11). | E6
26 | Freire, R. C., . (2020). “Neurostimulation in Anxiety Disorders, Post-traumatic Stress Disorder, and Obsessive-Compulsive Disorder.” [underlined: Advances in Experimental Medicine & Biology] 1191: 331–346.32002936 | E6
27 | Fryml, L. D., . (2018). “The role of rTMS for patients with severe PTSD and depression.” Evidence-Based Mental Health 21(1): 39–40.29305359 | E5
28 | Gao, F., . (2017). “Repetitive transcranial magnetic stimulation for pain after spinal cord injury: a systematic review and meta-analysis.” [underlined: Journal of Neurosurgical Sciences] 61(5): 514–522.27603408 | E7
29 | Geraets, C. N. W., . (2019). “Lack of analgesic effects of transcranial pulsed electromagnetic field stimulation in neuropathic pain patients: A randomized double-blind crossover trial.” Neuroscience Letters 699: 212–216.30710664 | E2
30 | Geraets, C. N. W., . (2019). “Lack of analgesic effects of transcranial pulsed electromagnetic field stimulation in neuropathic pain patients: A randomized double-blind crossover trial.” Neuroscience Letters 699: 212–216.30710664 | E1
31 | Gertler, P., . (2015). “Non-pharmacological interventions for depression in adults and children with traumatic brain injury.” [underlined: Cochrane Database of Systematic Reviews](12): CD009871. | E7
32 | Goudra, B., . (2017). “Repetitive Transcranial Magnetic Stimulation in Chronic Pain: A Meta-analysis.” [underlined: Albang Maqalat Wa Abhat Fi Altahdir Waalinas] 11(3): 751–757. | E7
33 | Gouveia, F. V., . (2020). “Treating Post-traumatic Stress Disorder with Neuromodulation Therapies: Transcranial Magnetic Stimulation, Transcranial Direct Current Stimulation, and Deep Brain Stimulation.” [underlined: Neurotherapeutics] 28: 28. | E7
34 | Hamid, P., . (2019). “Noninvasive Transcranial Magnetic Stimulation (TMS) in Chronic Refractory Pain: A Systematic Review.” [underlined: Cureus] 11(10): e6019.31824787 | E7
35 | Hammoud, M. and M. Milad (2018). “Symptom Changes in Posttraumatic Stress Disorder and Major Depressive Disorder After Transcranial Magnetic Stimulation: Mechanisms of Where and How in the Brain.” [underlined: Biological Psychiatry] 83(3): 200–202.29277191 | E6
36 | Hayashi, C., . (2019). “Abstract #77: repetitive Transcranial Magnetic Stimulation (rTMS) in chronic diffuse axonal injury: a randomized controlled trial.” [underlined: Brain Stimulation] 12(2): e27-. | E6
37 | Henssen, D., . (2019). “Bilateral vs unilateral repetitive transcranial magnetic stimulation to treat neuropathic orofacial pain: A pilot study.” [underlined: Brain Stimulation] 12(3): 803–805.30772275 | E9
38 | Herrero Babiloni, A., . (2018). “Non-invasive brain stimulation in chronic orofacial pain: a systematic review.” [underlined: Journal of pain research] 11: 1445–1457.30122975 | E7
39 | Herrold, A., . (2014). “Transcranial magnetic stimulation: potential treatment for co-occurring alcohol, traumatic brain injury and posttraumatic stress disorders.” [underlined: Neural Regeneration Research] 9(19): 1712–1730.25422632 | E6
40 | Hosomi, K., . (2019). “P74-S A randomized clinical trial of repetitive transcranial magnetic stimulation for neuropathic pain.” [underlined: Clinical Neurophysiology] 130(7): e114-. | E6
41 | Hosomi, K., . (2019). “Exploratory study of optimal conditions of repetitive transcranial magnetic stimulation of the primary motor cortex for chronic pain.” [underlined: Brain Stimulation] 12(2): 454-. | E6
42 | Kan, R. L. D., . (2020). “Non-invasive brain stimulation for posttraumatic stress disorder: a systematic review and meta-analysis.” [underlined: Transl Psychiatry Psychiatry] 10(1): 168. | E7
43 | Kaplan, C. M., . (2020). “Targeting network hubs with noninvasive brain stimulation in patients with fibromyalgia.” [underlined: Pain] 161(1): 43–46.31490327 | E6
44 | Karsen, E. F., . (2014). “Review of the effectiveness of transcranial magnetic stimulation for post-traumatic stress disorder.” [underlined: Brain Stimulation] 7(2): 151–157.24486424 | E7
45 | Keays, A. C. (2020). “190 Treating Fibromyalgia Syndrome through Neuromodulation With Transcranial Magnetic Stimulation.” [underlined: Cns Spectrums] 25(2): 319. | E6
46 | Kohutova, B., . (2017). “Theta burst stimulation in the treatment of chronic orofacial pain: a randomized controlled trial.” [underlined: Physiological Research] 66(6): 1041–1047.28937248 | E9
47 | Kumar, A., . (2017). “Targeting motor cortex with neuronavigated repetitive transcranial magnetic stimulation in management of chronic migraine.” [underlined: Indian journal of physiology and 6pharmacology] 1(5): 115–116 | E10
48 | Kumru, H., . (2017). “Effectiveness of repetitive trancranial or peripheral magnetic stimulation in neuropathic pain.” [underlined: Disability & Rehabilitation] 39(9): 856–866.27494799 | E7
49 | Lage, C., . (2016). “A systematic review of the effects of low-frequency repetitive transcranial magnetic stimulation on cognition.” [underlined: Journal of Neural Transmission] 123(12): 1479–1490.27503083 | E7
50 | Larkin, M. B., . (2020). “Neurostimulation for treatment-resistant posttraumatic stress disorder: an update on neurocircuitry and therapeutic targets.” [underlined: Journal of Neurosurgery]: 1–9. | E7
51 | Lefaucheur, J. P., . (2020). “Evidence-based guidelines on the therapeutic use of repetitive transcranial magnetic stimulation (rTMS): An update (2014-2018).” [underlined: Clinical Neurophysiology] 131(2): 474–528.31901449 | E6
52 | Leung, A., . (2020). “Transcranial Magnetic Stimulation for Pain, Headache, and Comorbid Depression: INS-NANS Expert Consensus Panel Review and Recommendation.” [underlined: Neuromodulation] 23(3): 267–290.32212288 | E6
53 | Lin, J., . (2019). “Chronic repetitive transcranial magnetic stimulation (rTMS) on sleeping quality and mood status in drug dependent male inpatients during abstinence.” Sleep Medicine 58: 7–12.31042621 | E1
54 | Lopez-Trigo, J., . (2017). “Effect of repetitive high frequency transcranial magnetic stimulation on trigeminal neuralgia.” [underlined: Brain stimulation. Conference: 2nd international brain stimulation conference. Spain. Conference start:. 20170305] Conference end: 20170308 10(2): 532. | E6
55 | Martino Cinnera, A., . (2016). “Clinical effects of non-invasive cerebellar magnetic stimulation treatment combined with neuromotor rehabilitation in traumatic brain injury. A single case study.” Functional Neurology 31(2): 117–120.27358225 | E5
56 | Mavromatis, N., . (2020). “Combination of cortical and peripheral TBS with physical therapy in chronic low back pain: after-effects on clinical and TMS outcomes.” [underlined: Clinical Neurophysiology] 131(4): e136-. | E6
57 | Mo, J. J., . (2019). “Motor cortex stimulation: a systematic literature-based analysis of effectiveness and case series experience.” BMC Neurology 19(1): 48.30925914 | E2
58 | Mori, N., . (2019). “P75-S Exploratory study of optimal stimulus parameters of repetitive transcranial magnetic stimulation for neuropathic pain.” [underlined: Clinical Neurophysiology] 130(7): e114-. | E6
59 | Nardone R, S. L., Versace V, Brigo F, Golaszewski S, Manganotti P, Saltuari L, Trinka E (2020). “Repetitive transcranial magnetic stimulation in traumatic brain injury: Evidence from animal and human studies.” [underlined: Brain Research Bulletin] 159: 44–52.32251693 | E7
60 | Nardone, R., . (2017). “rTMS of the prefrontal cortex has analgesic effects on neuropathic pain in subjects with spinal cord injury.” [underlined: Spinal Cord] 55(1): 20–25.27241450 | E6
61 | Neville, I. S., . (2015). “Repetitive Transcranial Magnetic Stimulation (rTMS) for the cognitive rehabilitation of traumatic brain injury (TBI) victims: study protocol for a randomized controlled trial.” [underlined: Trials [Electronic Resource]] 16: 440. | E6
62 | Nurmikko, T., . (2017). “Comparison of local sensory effects associated with real and sham TMS.” [underlined: Brain Stimulation] 10(2): 455-. | E4
63 | Nurmikko T, . (2019). “Enhanced functional connectivity within primary motor cortex correlates with pain relief induced by repetitive transcranial magnetic stimulation (RTMS).” [underlined: Neuromodulation] 22(7): e445-. | E6
64 | Pape, T., . (2019). “ReEnabling ConsciOus behaViors by Engaging dopamineRgic pathwaYs (RECOVERY).” [underlined: Brain Stimulation] 12(2): 559-. | E6
65 | Pink, A. E., . (2019). “The use of repetitive transcranial magnetic stimulation (rTMS) following traumatic brain injury (TBI): A scoping review.” [underlined: Neuropsychological Rehabilitation]: 1–27. | E7
66 | Paxman, E., . (2018). “Repetitive transcranial magnetic stimulation (rTMS) as a treatment for chronic dizziness following mild traumatic brain injury.” BMJ Case Reports 05: 05. | E5
67 | Pommier, B., . (2018). “Added value of multiple versus single sessions of repetitive transcranial magnetic stimulation in predicting motor cortex stimulation efficacy for refractory neuropathic pain.” Journal of Neurosurgery: 1–12. | E2
68 | Qui X, B. Y. (2019). “Manual lymphatic drainage combined with repetitive transcranial magnetic stimulation for post-stroke type I complex regional pain syndrome: a randomized controlled trial.” | E10
69 | Rodger J, S. R. (2015). “Optimising repetitive transcranial magnetic stimulation for neural circuit repair following traumatic brain injury.” [underlined: Neural Regeneration Research] 10(3): 357–359.25878575 | E6
70 | Rosenow, J., . (2019). “Amantadine + RTMS as a neurotherapeutic for disordered consciousness after TBI: safety findings.” [underlined: Neuromodulation] 22(3): E202-. | E6
71 | Rutherford, G., . (2017). “RTMS as a treatment for mild traumatic brain injury.” [underlined: Brain Stimulation] 10(2): 481-. | E6
72 | Sahlem, G., . (2017). “Dorsolateral prefrontal cortex transcranial magnetic stimulation as a tool to decrease pain and craving in opiate dependent individuals: a pilot study of feasibility and effect size.” [underlined: Brain Stimulation] 10(2): 482-. | E6
73 | Selingardi, P. M. L., . (2019). “Long-term deep-TMS does not negatively affect cognitive functions in stroke and spinal cord injury patients with central neuropathic pain.” BMC Neurology 19(1): 319.31823735 | E4
74 | Seminowicz, D. A., . (2018). “Left dorsolateral prefrontal cortex repetitive transcranial magnetic stimulation reduces the development of long-term muscle pain.” Pain 159(12): 2486–2492.30431520 | E1
75 | Shafiee, S., . (2017). “Repetitive transcranial magnetic stimulation: a potential therapeutic modality for chronic low back pain.” [underlined: The Korean journal of pain] 30(1): 71–72.28119775 | E6
76 | Shin, S. S., . (2018). “Transcranial magnetic stimulation and environmental enrichment enhances cortical excitability and functional outcomes after traumatic brain injury.” Brain Stimulation 11(6): 1306–1313.30082198 | E1
77 | Siddiqi, S., . (2019). “Functional connectivity changes with targeted rTMS of the dorsal attention network in TBI-associated depression.” [underlined: Brain Stimulation] 12(2): 538-. | E6
78 | Siddiqi, S. H., . (2019). “Individualized Connectome-Targeted Transcranial Magnetic Stimulation for Neuropsychiatric Sequelae of Repetitive Traumatic Brain Injury in a Retired NFL Player.” [underlined: Journal of Neuropsychiatry & Clinical Neurosciences] 31(3): 254–263. | E6
79 | Tallus, J., . (2013). “Transcranial magnetic stimulation-electroencephalography responses in recovered and symptomatic mild traumatic brain injury.” Journal of Neurotrauma 30(14): 1270–1277.23384582 | E4
80 | Taheri, A., . (2017). “Repetitive Transcranial Magnetic Stimulation for Phantom Limb Pain: Probably Effective but Understudied.” [underlined: Neuromodulation] 20(1): 88–89.28101993 | E6
81 | Tanwar, S., . (2020). “Effect of transcranial magnetic stimulation on noxious cold mediated pain modulation in fibromyalgia syndrome.” [underlined: Brain Stimulation] 10(2): 471-. | E6
82 | Tendler, A., . (2017). “How to Use the H1 Deep Transcranial Magnetic Stimulation Coil for Conditions Other than Depression.” [underlined: Journal of Visualized Experiments] 119(01): 23. | E6
83 | Tiwari, V., . (2019). “Effect of rTMS therapy on pain descriptors and corticomotor excitability in fibromyalgia: a randomized control trial.” [underlined: Brain Stimulation] 12(2): 495-. | E6
84 | Tolonen, A., . (2018). “Quantitative EEG Parameters for Prediction of Outcome in Severe Traumatic Brain Injury: Development Study.” Clinical EEG & Neuroscience: Official Journal of the EEG & Clinical Neuroscience Society (ENCS) 49(4): 248–257. | E2
85 | Trevizol, A. P., . (2016). “Transcranial magnetic stimulation for posttraumatic stress disorder: an updated systematic review and meta-analysis.” [underlined: Trends in Psychiatry & Psychotherapy] 38(1): 50–55.27074341 | E7
86 | Villamar, M. F., . (2012). “Noninvasive brain stimulation to modulate neuroplasticity in traumatic brain injury.” [underlined: Neuromodulation] 15(4): 326–338.22882244 | E6
87 | Wahbeh, H., . (2014). “Complementary and Alternative Medicine for Posttraumatic Stress Disorder Symptoms: A Systematic Review.” [underlined: Journal of Evidence-Based Complementary & Alternative Medicine] 19(3): 161–175.24676593 | E7
88 | Walter, A., . (2020). “Repetitive transcranial magnetic stimulation as treatment for neuropathic pain in patients with spinal cord injury.” Journal of Neurosurgical Sciences 64(4): 404–405.31111722 | E10
89 | Wilkes, S., . (2020). “Impacts of rTMS on Refractory Depression and Comorbid PTSD Symptoms at a Military Treatment Facility.” Military Medicine 03: 03. | E1
90 | Wout-Frank, M., . (2019). “TBS-Modulated Anger in Veterans With PTSD.” [underlined: Biological Psychiatry] 85(10): S217-. | E6
91 | Yan, T., . (2017). “Different frequency repetitive transcranial magnetic stimulation (rTMS) for posttraumatic stress disorder (PTSD): A systematic review and meta-analysis.” [underlined: Journal of Psychiatric Research] 89: 125–135.28278422 | E7
92 | Yani, M. S., . (2019). “Motor cortical neuromodulation of pelvic floor muscle tone: Potential implications for the treatment of urologic conditions.” Neurourology & Urodynamics 38(6): 1517–1523.31044482 | E4
93 | Yang, S. and M. C. Chang (2020). “Effect of Repetitive Transcranial Magnetic Stimulation on Pain Management: A Systematic Narrative Review.” [underlined: Frontiers in neurology [electronic resource].] 11: 114. | E7
94 | Young, J. R., . (2020). “Non-invasive brain stimulation modalities for the treatment and prevention of opioid use disorder: a systematic review of the literature.” [underlined: Journal of Addictive Diseases] 38(2): 186–199.32469286 | E7
95 | Zhang, J. J. Q., . (2019). “Effects of repetitive transcranial magnetic stimulation (rTMS) on craving and substance consumption in patients with substance dependence: a systematic review and meta-analysis.” [underlined: Addiction] 114(12): 2137–2149.31328353 | E7
96 | (2019). “CTMSS 2019 Annual Meeting.” [underlined: Brain Stimulation] 12(4): A1–A10. | E6

### APPENDIX D STUDIES INCLUDED IN EXISTING SYSTEMATIC REVIEW (O’CONNELL 2018)

Author, Year | Methods | Participants | Interventions | Outcomes
Ahmed 2011^1^ | Parallel, quasi-RCT | Country of study: Egypt; Setting: Dept of Neurology, hospital-based; Condition: chronic phantom limb pain; Prior management details: unresponsive to various pain medications n = 27, 17 active and 10 sham; Age, mean (SD): active group 52.01 (12.7) years, sham group 53.3 (13.3) years; Duration of symptoms, mean (SD) months: active group 33.4 (39.3), sham group 31.9 (21.9); Gender distribution: active group 13 M, 4 F; sham group 6 M, 4 F | Stimulation type: rTMS; Stimulation parameters: frequency 20 Hz; coil orientation not specified, number of trains 10; duration of trains 10 s; ITI 50 s; total number of pulses 2000; Stimulation location: M1 stump region; Number of treatments: x 5, daily; Control type: sham - coil angled away from scalp | Primary: pain VAS (anchors not reported), LANNS; When taken: poststimulation session 1 and 5 and at 1 month and 2 months post-treatment; Secondary: none relevant
Andre-Obadia 2006^2^ | Cross-over RCT; 3 conditions | Country of study: France; Setting: laboratory; Condition: neuropathic pain (mixed central, peripheral and facial); Prior management details: refractory to drug management, candidates for invasive; MCS n=14; Age: 31-66 years; mean 53 (SD 11); Duration of symptoms: mean 6.9 years (SD 4); Gender distribution: 10 M, 4 F | Stimulation type: rTMS figure-of-8 coil; Stimulation parameters:; Condition 1: frequency 20 Hz; coil orientation posteroanterior; 90% RMT; number of trains 20; duration of trains 4 s; ITI 84 s; total number of pulses 1600; Condition 2: frequency 1 Hz; coil orientation lateromedial; number of trains 1; duration of trains 26 min, total number of pulses 1600; Condition 3: sham - same as for condition 2 with coil angled away perpendicular to scalp; Stimulation location: M1 contralateral to painful side; Number of treatments: 1 for each condition | Primary: VAS 0-10 cm, anchors “no pain” to “unbearable pain”; When taken: immediately poststimulation then daily for 1 wk; Secondary: none
Andre-Obadia 2008^3^ | Cross-over RCT; 3 conditions | Country of study: France; Setting: laboratory-based; Condition: neuropathic pain (mixed central, peripheral and facial); Prior management details: refractory to drug management, candidates for invasive; MCS; n = 30; Age: 31-72 years, mean 55 (SD 10.5); Duration of symptoms: mean 5 years (SD 3.9); Gender distribution: 23 M, 7 F | Stimulation type: rTMS, figure-of-8 coil; Stimulation parameters:; Condition 1: frequency 20 Hz; coil orientation posteroanterior; 90% RMT; number of trains 20; duration of trains 4 s; ITI 84 s; total number of pulses 1600; Condition 2: frequency 20 Hz, coil orientation lateromedial; number of trains 20; duration of trains 4 s;; ITI 84 s; total number of pulses 1600; Condition 3: sham - same as for active conditions with coil angled away perpendicular to scalp; Stimulation location: M1 contralateral to painful side; Number of treatments: 1 for each condition | Primary: 0-10 NRS (anchors “no pain” to “unbearable pain”); When taken: daily for 2 wks poststimulation; Secondary: none
Andre-Obadia 2011^4^ | Cross-over RCT; 3 conditions | Country of study: France; Setting: laboratory-based; Condition: chronic neuropathic pain (mixed); Prior management details: resistant to conventional pharmacological treatment; n = 45; Age: 31-72 years (mean 55); Duration of symptoms: “chronic”; Gender distribution: 28 M, 17 F | Stimulation type: rTMS; Stimulation parameters: frequency 20 Hz; coil orientation not specified, number of trains 20; duration of trains 4 s; ITI 84 s; total number of pulses 1600; Stimulation location: M1 hand area; Number of treatments: 1 per group; Control type: sham coil - same sound and appearance, no control for sensory cues | Primary: pain NRS anchors 0 = no pain, 10 = unbearable pain; When taken: daily for 2 wks following each stimulation; Secondary: none relevant
Avery 2013^5^ | Parallel RCT | Country of study: USA; Setting: unclear; Condition: chronic widespread pain; Prior management details: not reported; n = 19; Age mean (SD): active 54.86 (7.65) years, sham 52.09 (10.02) years; Duration of symptoms (months mean (SD)): active group 11 (4.26), sham group 15.64 (6.93); Gender distribution: all F | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation not specified; 120% RMT; number of trains 75; duration of trains 4 s; ITI 26 s; total number of pulses 3000; Stimulation location: L DLPFC; Number of treatments: 15 sessions over 4 wks; Control type: sham coil - controls for visual, auditory and scalp sensory cues | Primary: pain NRS 0-10 anchors not reported; When taken: end of treatment period, 1 month following and 3 months following; Secondary: pain interference BPI; QoL SF-36; AEs: multiple minor; no clear difference in incidence between active and sham stimulation
Borckardt 2009^6^ | Cross-over RCT; 2 conditions | Country of study: USA; Setting: laboratory; Condition: peripheral neuropathic pain; Prior management details: not specified; n = 4; Age: 33-58 years; mean 46 (SD 11); Duration of symptoms: 5-12 years; mean 10.25 (SD 3.5); Gender distribution: 1 M, 3 F | Stimulation type: rTMS, figure-of-8 coil; Stimulation parameters: frequency 10 Hz; coil orientation not specified; 100% RMT; number of trains 40; duration of trains 10 s; ITI 20 s; total number of pulses 4000; Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation anteroposterior; 90% RMT; number of trains 20; duration of trains 10 s; ITI 50 s; total number of pulses 2000; Stimulation location: L M1; Number of treatments: 14 sessions. 10 sessions in 2 wks followed by maintenance phase of 1 session at wks 4, 6, 8 and 10; Control type: sham coil - did not control for sensory cues | Primary: average daily pain 0-10 Likert scale, anchors “no pain at all” to “worst pain imaginable”; When taken: post-stimulation for each condition (unclear how many days post) and daily for 3 wks poststimulation; Secondary: none
Boyer 2014^7^ | Parallel RCT | Country of study: France; Setting: specialised pain treatment centre; Condition: fibromyalgia; Prior management details: stable treatment for more than 1 month before enrolment; n = 38; Age, mean (SD): active group 49.1 (10.6) years, sham group 47.7 (10.4) years; Duration of symptoms, mean (SD): active group 3.7 (4.5) years, sham group 3.6 (3.8); Gender distribution: 37 F, 1 M | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation anteroposterior; 90% RMT; number of trains 20; duration of trains 10 s; ITI 50 s; total number of pulses 2000; Stimulation location: L M1; Number of treatments: 14 sessions. 10 sessions in 2 wks followed by maintenance phase of 1 session at wks 4, 6, 8 and 10; Control type: sham coil - did not control for sensory cues | Primary: pain VAS 0 = no pain, 10 = maximal pain imaginable; When taken: 2 wks, 11 wks; Secondary: FIQ; AEs
Carretero 2009^8^ | Parallel RCT | Country of study: Spain; Setting: outpatient clinic; Condition: fibromyalgia (with major depression); Prior management details: unclear; n = 26; Age: active group 47.5 (SD 5.7) years, sham group 54.9 (SD 4.9) years; Duration of symptoms: unclear “chronic”; Gender distribution: 2 M, 24 F | Stimulation type: rTMS; Stimulation parameters: frequency 1 Hz; coil orientation not specified; 110% RMT; number of trains 20; duration of trains 60 s; ITI 45 s; number of pulses 1200; Stimulation location: R DLPFC; Number of treatments: up to 20 on consecutive working days; Control type: coil angled 45º from the scalp | Primary: Likert pain scale 0-10, anchors “no pain” to “extreme pain”; When taken: 2 wks, 4 wks and 8 wks from commencement of study; Secondary: none
Dall’Agnol 2014^9^ | Parallel RCT | Country of study: Brazil; Setting: not specified; Condition: chronic myofascial pain in the upper body; Prior management details: not reported; n = 24; Age, mean (SD): active group 45.83 (9.63) years, sham group 44.83 (14.09) years; Duration of symptoms: not reported; Gender distribution: all F | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation 45° from midline, 80% RMT, number of trains 16; duration of trains 10 s; ITI 26 s; total number of pulses 1600; Stimulation location: L M1; Number of treatments: 10 sessions, timescale not specified; Control type: sham coil - same sound and appearance and sensation | Primary: pain NRS anchors 0 = no pain, 10 = worst possible pain; When taken: postintervention; Secondary: AEs
de Oliveira 2014^10^ | Parallel RCT | Country of study: Brazil; Setting: neurology dept; Condition: CPSP; Prior management details: stable medication for 30 d preceding baseline; n = 23; Age, mean (SD): active group 55 (9.67) years, sham group SD 57.8 (11.86) years; Duration of symptoms, mean (SD): active group 64.18 (49.27) months, sham group 50.1 (28.04); Gender distribution: active group 45% M, sham group 50% M | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation not specified, 120% RMT, number of trains 25; duration of trains 5 s; ITI 25s; total number of pulses 1250; Stimulation location: L premotor/DLPFC; Number of treatments: 10 sessions daily for 2 wks; Control type: sham coil - same sound and appearance, no control for sensory cues | Primary: pain NRS anchors not reported; When taken: end of intervention, 1, 2, and 4 wks postintervention; Secondary: AEs, QoL (SF-36)
Defrin 2007^11^ | Parallel RCT | Country of study: Israel; Setting: outpatient department; Condition: post-SCI central neuropathic pain; Prior management details: refractory to drug, physical therapy and complementary therapy management; n = 12; Age: 44-60 years; mean 54 (SD 6); Duration of symptoms: > 12 months; Gender distribution: 7 M, 4 F | Stimulation type: rTMS, figure-of-8 coil; Stimulation parameters: frequency 5 Hz; coil orientation not specified; 115% RMT; number of trains 500; duration of trains 10 s; ITI 30 s; total number of pulses 500 reported, likely to have been 25,000 judging by these parameters; Stimulation location: M1 - midline; Number of treatments: x 10, x 1 daily on consecutive days; Control type: sham coil - visually the same and makes similar background noise | Primary: 15 cm 0-10 VAS pain intensity, anchors “no pain sensation” to “most intense pain sensation”; When taken: pre and post each stimulation session; Secondary: McGill pain questionnaire; When taken: 2- and 6-wk follow-up period
Fregni 2005^12^ | Cross-over RCT | Country of study: USA; Setting: laboratory; Condition: chronic pancreatitis pain; Prior management details: not specified; n = 5; Age: 44 (SD 11); Duration of symptoms: not specified, “chronic”; Gender distribution: not specified | Stimulation type: rTMS, figure-of-8 coil; Stimulation parameters: frequency 1 Hz or 20 Hz; coil orientation not specified; 90% RMT; number of trains not specified; duration of trains not specified; ITI not specified; total number of pulses 1600; Stimulation location: L and R SII; Number of treatments: 1 for each condition; Control type: sham, “specially designed sham coil”. No further details | Primary: pain VAS, anchors not specified; When taken: after each stimulation session; Secondary: none
Fregni 2011^13^ | Parallel RCT | Country of study: USA; Setting: laboratory; Condition: chronic visceral pain (chronic pancreatitis); Prior management details: most on continuous opioid therapy, most had received surgery for their pain; n = 17, 9 in active group, 8 in sham group; Age mean (SD): active group 41.11 (11.27) years, sham group 46.71 (13.03) years; Duration of symptoms: > 2 years; Gender distribution: 14 F, 3 M | Stimulation type: rTMS; Stimulation parameters: frequency 1 Hz; coil orientation not specified, number of trains 1; duration of trains not specified; intensity 70% maximum stimulator output, total number of pulses 1600; Stimulation location: SII; Number of treatments: 10, x 1 daily (wkdays only); Control type: sham rTMS coil | Primary: pain VAS; 0 = no pain, 10 = most intense pain imaginable; When taken: daily pain logs for 3 wks pre-intervention, daily post-stimulation during intervention period and at 3-wk follow-up; Secondary: none relevant
Hirayama 2006a^14^ | Cross-over RCT; 5 conditions | Country of study: Japan; Setting: laboratory; Condition: intractable deafferentation pain (mixed central, peripheral and facial); Prior management details: intractable; n = 20; Age: 28-72 years; Duration of symptoms: 1.5-24.3 years, mean 6.4 (SD 6); Gender distribution: 13 M, 7 F | Stimulation type: rTMS, figure-of-8 coil; Stimulation parameters: frequency 5 Hz; coil orientation not specified; 90% RMT; number of trains 10; duration of trains 10 s; ITI 50 s; total number of pulses 500; Stimulation location: condition 1: M1; condition 2: primary sensory cortex; condition 3: pre-motor area; condition 4: supplementary motor area; condition 5: sham; Number of treatments: 1 for each condition; Control type: coil angled 45º from scalp with synchronised electrical scalp stimulations to mask sensation | Primary: pain intensity VAS, anchors not specified; When taken: 0, 30, 60, 90, 180 min poststimulation Secondary: None
Hosomi 2013^15^ | Cross-over RCT | Country of study: Japan; Setting: multicentre, laboratory-based; Condition: mixed neuropathic pain; Prior management details: pain persisted despite “adequate treatments”; n = 70 of whom 64 analysed; Age mean (SD): 60.7 (10.6) years; Duration of symptoms: 58.2 (10.6) months; Gender distribution: 40 M, 24 F | Stimulation type: rTMS; Stimulation parameters: frequency 5 Hz; coil orientation parasagittal, number of trains 10; duration of trains 10 s; ITI 50 s, intensity 90% RMT, total number of pulses per session 500; Stimulation location: M1 corresponding to painful region; Number of treatments: 10, x 1 daily (consecutive working days); Control type: sham coil | Current daily pain 0-100 VAS (anchors not reported), SF McGill, AEs
Irlbacher 2006^16^ | Cross-over RCT; 3 conditions | Country of study: Germany; Setting: laboratory; Condition: PLP and CNP; Prior management details: unclear; n = 27; Age: (median) PLP 46.6 years, CNP 51.1 years; Duration of symptoms: mean PLP 15.2 (SD 14.8), CNP 3.9 (SD 4.1) years.; Gender distribution: 16 M, 11 F | Stimulation type: rTMS, figure-of-8 coil; Stimulation parameters:; Condition 1: frequency 1 Hz; coil orientation not specified; 95% RMT; number of trains not specified; duration of trains not specified; ITI not specified; total number of pulses 500; Condition 2: frequency 5 Hz; coil orientation not specified; 95% RMT; number of trains not specified; duration of trains not specified; ITI not specified; total number of pulses 500; Condition 3: sham frequency 2 Hz; coil orientation not specified; number of trains not specified; duration of trains not specified; ITI not specified; total number of pulses 500; Stimulation location: M1, contralateral to painful side; Number of treatments: x 1 for each condition; Control type: sham coil; mimics sight and sound of active treatment | Primary: 0-100 mm VAS pain intensity, anchors “no pain” and “most intense pain imaginable”; When taken: pre- and post-stimulation; Secondary: none
Jette 2013^17^ | Cross-over RCT | Country of study: Canada; Setting: outpatient rehabilitation centre; Condition: post-SCI neuropathic pain; Prior management details: almost all participants in various medications; n = 18; Age: range 31-69 years, mean (SD) 50 (9); Duration of symptoms: not reported; Gender distribution: 11 M, 5 F | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation 45º posterolateral, 90%; RMT for hand, 110%; RMTA for leg, number of trains 40; duration of trains 5 s; ITI 25 s; total number of pulses 2000; Stimulation location: M1 hand or leg area with neuronavigation; Number of treatments: single session per condition, 1 session of sham; Control type: sham coil - same sound and appearance and sensation | Primary: pain NRS anchors 0 = no pain, 10 = worst possible pain; When taken: immediately poststimulation, 20 min poststimulation; Secondary: AEs - though no formal assessment reported
Kang 2009^18^ | Cross-over RCT | Country of study: South Korea; Setting: university hospital outpatient setting; Condition: post-SCI central neuropathic pain; Prior management details: resistant to drug, physical or complementary therapies; n = 11; Age: 33-75 years, mean 54.8; Duration of symptoms: chronic; Gender distribution: 6 M, 5 F | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation angled 45° posterolaterally; 80% RMT; number of trains 20; duration of trains 5 s; ITI 55 s; total number pulses 1000; Stimulation location: R M1, hand area; Number of treatments: 5, x 1 daily; Control type: coil elevated and angled away from the scalp | Primary: NRS average pain over last 24 h, anchors “no pain sensation” to “most intense pain sensation imaginable”; When taken: immediately after the 3rd and 5th treatments and 1, 3, 5, and 7 wks after the end of the stimulation period
Khedr 2005^19^ | Parallel RCT | Country of study: Egypt; Setting: university hospital neurology department; Condition: neuropathic pain, mixed central (poststroke) and facial (trigeminal neuralgia) pain; Prior management details: refractory to drug management; n = 48; Age: poststroke 52.3 (SD 10.3) years, trigeminal neuralgia 51.5 (SD 10.7) years; Duration of symptoms: poststroke 39 months (SD 31), trigeminal neuralgia 18 months (SD 17); Gender distribution: 8 M, 16 F | Stimulation type: rTMS; Stimulation parameters: frequency 20 Hz; coil orientation not specified; 80% RMT; number of trains 10; duration of trains 10 s; ITI 50 s; total number of pulses 2000; Stimulation location: M1 contralateral to the side of worst pain; Number of treatments: 5, x 1 on consecutive days; Control type: coil elevated and angled away from scalp | Primary: pain VAS, anchors not specified; When taken: post 1st, 4^th^, and 5th stimulation session and 15 days after the last session; Secondary: none
Lee 2012^20^ | Parallel RCT | Country of study: Korea; Setting: outpatient clinic; Condition: fibromyalgia; Prior management details: none reported; n = 22; Age mean (SD): low-frequency group 45.6 (9.6) years, high-frequency group 53 (4.2) years, sham group 51.3 (6.2) years; Duration of symptoms (months mean (SD)): low-frequency group: 47.2 (20.1), high-frequency group 57.1 (6.4), sham group 44.7 (10.3); Gender distribution: all F | Stimulation type: rTMS; Stimulation parameters:; Low-frequency group: frequency 1 Hz; coil orientation not specified, number of trains 2; duration of trains 800 s; ITI 60 s; total number of pulses 1600; High-frequency group: frequency 10 Hz; coil orientation not specified, number of trains 25; duration of trains 8 s; ITI 10 s; total number of pulses 2000; Stimulation location: right DLPFC (low-frequency), L M1 (high-frequency); Number of treatments: 10, x 1 daily (wkdays only) for 2 wks; Control type: sham - coil orientated away from scalp | Primary: 0-100 mm pain VAS; 0 = none, 100 = an extreme amount of pain; When taken: post-treatment and at 1 month follow-up Secondary: FIQ
Lefaucheur 2001a^21^ | Cross-over RCT | Country of study: France; Setting: laboratory; Condition: intractable neuropathic pain (mixed central and facial); Prior management details: refractory to drug management; n = 14; Age: 34-80 years, mean 57.2; Duration of symptoms: not specified “chronic”; Gender distribution: 6 M, 8 F | Stimulation type: rTMS, figure-of-8 coil; Stimulation parameters: frequency 10 Hz; coil orientation not specified; 80% RMT; number of trains 20; duration of trains 5 s; ITI 55 s; total number of pulses 1000; Stimulation location: M1, contralateral to painful side; Number of treatments: x 1 for each condition; Control type: sham coil used (inert) | Primary: 0-10 VAS, anchors not specified; When taken: daily for 12 days poststimulation; Secondary: none
Lefaucheur 2001b^22^ | Cross-over RCT | Country of study: France; Setting: laboratory; Condition: neuropathic pain (mixed central and peripheral); Prior management details: refractory to drug management; n = 18; Age: 28-75 years, mean 54.7; Duration of symptoms: not specified “chronic”; Gender distribution: 11 M, 7 F | Stimulation type: rTMS, figure-of-8 coil; Stimulation parameters:; Condition 1: frequency 10 Hz; coil orientation posteroanterior; 80% RMT; number of trains 20; duration of trains 5 s; ITI 55 s; total number of pulses 1000; Condition 2: frequency 0.5 Hz; coil orientation posteroanterior; number of trains 1; duration of trains 20 min; total number of pulses 600; Condition 3: sham - same as for condition 1 with sham coil; Stimulation location: M1 contralateral to painful side; Number of treatments: x 1 for each condition | Primary: 0-10 VAS pain, anchors not specified; When taken: 5-10 min poststimulation; Secondary: none
Lefaucheur 2004^23^ | Cross-over RCT | Country of study: France; Setting: laboratory; Condition: neuropathic pain (mixed central, peripheral and facial); Prior management details: refractory to drug management; n = 60; Age: 27-79 years, mean 54.6; Duration of symptoms: not specified “chronic”; Gender distribution: 28 M, 32 F | Stimulation type: rTMS, figure-of-8 coil; Stimulation parameters: frequency 10 Hz; coil orientation posteroanterior; 80% RMT; number of trains 20; duration of trains 5 s; ITI 55 s; total number of pulses 1000; Stimulation location: M1 contralateral to painful side; Number of treatments: x 1 for each condition; Control type: sham coil | Primary: 0-10 VAS pain, anchors not specified; When taken: 5 min poststimulation; Secondary: none
Lefaucher 2006^24^ | Cross-over RCT; 3 conditions | Country of study: France; Setting: laboratory; Condition: unilateral chronic neuropathic pain (mixed central and peripheral); Prior management details: refractory to drug management; n = 22; Age: 28-75 years, mean 56.5 (SD 2.9); Duration of symptoms: 2-18 years, mean 5.4 (SD 4.1); Gender distribution: 12 M, 10 F | Stimulation type: rTMS, figure-of-8 coil; Stimulation parameters:; Condition 1: frequency 10 Hz; coil orientation posteroanterior; 90% RMT; number of trains 20; duration of trains 6 s; ITI 54 s; total number of pulses 1200; Condition 2: frequency 1 Hz; coil orientation posteroanterior; 90% RMT; number of trains 1; duration of trains 20 min; total number of pulses 1200; Condition 3: sham coil; Stimulation location: M1 contralateral to painful side; Number of treatments: x 1 for each condition | Primary: 0-10 VAS pain, anchors not specified; When taken: pre- and poststimulation; Secondary: none
Lefaucher 2008^25^ | Cross-over RCT; 3 conditions | Country of study: France; Setting: laboratory; Condition: neuropathic pain (mixed central, peripheral and facial); Prior management details: refractory to drug management for at least 1 year; n = 46; Age: 27-79 years, mean 54.2; Duration of symptoms: chronic > 1 year; Gender distribution: 23 M, 23 F | Stimulation type: rTMS, figure-of-8 coil; Stimulation parameters:; Condition 1: frequency 10 Hz; coil orientation posteroanterior; 90% RMT; number of trains 20; duration of trains 6 s; ITI 54 s; total number of pulses 1200; Condition 2: frequency 1 Hz; coil orientation posteroanterior; 90% RMT; number of trains 1; duration of trains 20 min; total number of pulses 1200; Condition 3: sham coil; Stimulation location: M1 contralateral to painful side; Number of treatments: x 1 for each condition | Primary: 0-10 VAS, anchors not specified; When taken: pre- and poststimulation; Secondary: none
Malavera 2013^26^ | Parallel RCT | Country of study: Colombia; Setting: rehabilitation department; Condition: phantom limb pain; Prior management details: no difference across groups in use of NSAIDS, physical rehabilitation or psychological therapy; n = 54; Age, mean (SD): active group 33.1 (6.6) years, sham group 8.2 (6.3) years; Duration of symptoms: not reported; Gender distribution: 50 M, 4 F | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation 45° angle from midline, 90% RMT number of trains 20; duration of trains 6 s; ITI 54 s; total number of pulses 1200; Stimulation location: M1 contralateral to painful side, no neuronavigation Number of treatments: 10 sessions x 1 per work day for 2 wks; Control type: sham coil - same sound and appearance, no control for sensory cues | Primary: pain NRS anchors 0 = no pain, 10 = worst pain possible; When taken: 15 d and 30 d after treatment; Secondary: AEs
Medeiros 2016^27^ | Factorial RCT | Country of study: Brazil; Setting: not specified; Condition: chronic myofascial pain syndrome; Prior management details: not reported; n = 46, of which 23 relevant to this review; Age, mean (SD): active group 45.83 (9.63) years, sham group 46.73 (13.09) years; Duration of symptoms: not reported; Gender distribution: all F | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation 45° from midline, 80% RMT, number of trains not reported; duration of trains not reported; ITI s not reported; total number of pulses 1600; Stimulation location: L M1; Number of treatments: 10 days of stimulation; Control type: sham coil - no details provided | Primary: pain NRS anchors 0 = no pain, 10 = worst possible pain; When taken: at end of intervention; Secondary: none relevant
Mhalla 2011^28^ | Parallel RCT | Country of study: France Setting: laboratory; Condition: fibromyalgia; Prior management details: not reported but concomitant treatments allowed; n = 40; Age, mean (SD): active group 51.8 (11.6) years, sham group 49.6 (10) years; Duration of symptoms (mean (SD) years): active group 13 (12.9), sham group 14.1 (11.9); Gender distribution: all F | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation posteroanterior, number of trains 15; duration of trains 10 s; ITI 50 s, intensity 80% RMT, total number of pulses 1500; Stimulation location: L M1; Number of treatments: 14, x 1 daily for 5 days, x 1 wkly for 3 wks, x 1 every two wks for 6 wks, x 1 monthly for 3 months; Control type: sham coil, did not control for sensory cues | Primary: pain NRS; 0 = no pain, 10 = maximal pain imaginable; When taken: day 5, 3 wks, 9 wks, 21 wks, 25 wks; Secondary: BPI interference scale, FIQ
Nardone 2017^29^ | Parallel RCT | Country of study: Italy and Austria; Setting: laboratory; Condition: below level post SCI, predominantly neuropathic pain; Prior management details: > 4/10 pain despite rehabilitation and pharmacological treatment. All participants previously treated with antidepressant, anticonvulsants and analgesics for a minimum period of 6 months; n = 12; Age, mean (range): active group 43.7 (26-56) years, sham group 42.5 (24-62) years; Duration of symptoms: not reported; Gender distribution: 9 M, 3 F | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation AP direction, 120% RMT, number of trains 25; duration of trains 5 s; ITI 25s; total number of pulses 1250; Stimulation location: L PFC (no neuronavigation); Number of treatments: 10 sessions daily x 5 per wk for 2 wks; Control type: sham coil - same sound and appearance, no control for sensory cues | Primary: pain VAS anchors not reported When taken: postintervention, 1 month postintervention; Secondary: none relevant AEs
Nurmikko 2016^30^ | Cross-over RCT | Country of study: UK; Setting: laboratory; Condition: mixed refractory neuropathic pain; Prior management details: no benefit from medication or other stimulation approaches; n = 40 (27 after loss to follow-up); Age, range: 27-79 years; Duration of symptoms: not reported; Gender distribution: 23 M, 17 F | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation AP direction, 90% RMT, number of trains 20; duration of trains 10 s; ITI 1 min; total number of pulses 2000; Stimulation location: Site A: M1 hotspot, Site B M1 reorganised area, Site C (sham) occipital fissure; Number of treatments: 3-5 sessions per wk for 5 sessions; Control type: sham active stimulation of occipital fissure | Primary: pain NRS anchors 0 = no pain 10 = worst pain imagined; When taken: postintervention, 3 wks postintervention; Secondary: none relevant AEs
Onesti 2013^31^ | Cross-over RCT | Country of study: Italy; Setting: laboratory; n = 25; Condition: neuropathic pain from diabetic neuropathy; Prior management details: resistant to standard therapies for at least 1 year; Age mean (SD): 70.6 (8.5) years; Duration of symptoms (months mean (SD)): not reported; Gender distribution: 9 F, 14 M | Stimulation type: rTMS using H-coil; Stimulation parameters: frequency 20 Hz; coil orientation H coil, number of trains 30; duration of trains 2.5 s; ITI 30 s, intensity 100% RMT, total number of pulses 1500; Stimulation location: M1 lower limb (deep in central sulcus); Number of treatments: 5 per condition on consecutive days; Control type: sham coil, controlled for scalp sensory, auditory and visual cues | Primary: pain VAS 0-100, no pain to worst possible pain; When taken: immediately poststimulation, 3 wks poststimulation; Secondary: none relevant
Passard 2007^32^ | Parallel RCT | Country of study: France; Setting: laboratory; Condition: fibromyalgia; Prior management details: unclear; n = 30; Age: active group: 52.6 (SD 7.8) years, sham group 55.3 (SD 8.9) years; Duration of symptoms: active group: 8.1; (SD 7.9), sham group: 10.8 (SD 8.6); Gender distribution: 1 M, 29 F | Stimulation type: rTMS, figure-of-8 coil; Stimulation parameters: frequency 10 Hz; coil orientation posteroanterior; 80% RMT; number of trains 25; duration of trains 8 s; ITI 52 s; total number of pulses 2000; Stimulation location: M1 contralateral to painful side; Number of treatments: 10, x 1 daily for 10 working days; Control type: sham rTMS coil. Mimics sight and sound of active treatment | Primary: 0-10 NRS of average pain intensity over last 24 h, anchors “no pain” to “maximal pain imaginable”; When taken: daily during treatment period and at 15, 30, and 60 days post-treatment follow-up; Secondary: FIQ; When taken: as for primary outcome
Picarelli 2010^33^ | Parallel RCT | Country of study: Brazil; Setting: laboratory; Condition: CRPS type I; Prior management details: refractory to best medical treatment; n = 23; Age mean (SD): active group 43.5 (12.1) years, sham group 40.6 (9.9) years; Duration of symptoms (months mean (SD)): active group 82.33 (34.5), sham group 79.27 (32.1); Gender distribution: 14 F, 9 M | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation posteroanterior, number of trains 25; duration of trains 10 s; ITI 60 s, intensity 100% RMT, total number of pulses 2500; Stimulation location: M1 contralateral to painful limb; Number of treatments: 10, x 1 daily on consecutive wkdays; Control type: sham coil - did not control for sensory cues | Primary: pain VAS; 0 = “no pain”, 10 = “most severe pain”; When taken: after first and last session then 1 and 3 months post-treatment; Secondary: QoL SF-36, not reported
Pleger 2004^34^ | Cross-over RCT | Country of study: Germany; Setting: laboratory; Condition: CRPS type I; Prior management details: drug management ceased for 48 h prior to study; n = 10; Age: 29-72 years, mean 51; Duration of symptoms: 24-72 months, mean 35; Gender distribution: 3 M, 7 F | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation unspecified; 110% RMT; number of trains 10; duration of trains 1.2 s; ITI 10 s; total number of pulses 120; Stimulation location: M1 hand area; Number of treatments: 1 for each condition; Control type: coil angled 45º away from scalp | Primary: 0-10 VAS current pain intensity, anchors “no pain” to “most extreme pain”; When taken: 30 s, 15, 45, and 90 min poststimulation; Secondary: none; When taken: 30 s, 15, 45, and 90 min poststimulation
Rollnik 2002^35^ | Cross-over RCT | Country of study: Germany; Setting: pain clinic; Condition: chronic pain (mixed musculoskeletal and neuropathic); Prior management details: “intractable”; n = 12; Age: 33-67 years, mean 51.3 (SD 12.6); Duration of symptoms: mean 2.7 (SD 2.4); Gender distribution: 6 M, 6 F | Stimulation type: rTMS, circular coil for arm symptoms, double cone coil for leg symptoms; Stimulation parameters: frequency 20 Hz; coil orientation not specified; 80% RMT; number of trains 20; duration of trains 2 s; ITI not specified; total number of pulses 800; treatment duration 20 min; Stimulation location: M1 (midline); Number of treatments: x 1 for each condition; Control type: coil angled 45º away from the scalp | Primary: 0-100 mm VAS pain intensity, anchors “no pain” to “unbearable pain”; When taken: 0, 5, 10, and 20 min post-stimulation; Secondary: none
Saitoh 2007^36^ | Cross-over RCT; 4 conditions | Country of study: Japan; Setting: laboratory; Condition: neuropathic pain (mixed central and peripheral); Prior management details: intractable; n = 13; Age: 29-76 years, mean 59.4; Duration of symptoms: 2-35 years, mean 10.2 (SD 9.7); Gender distribution: 7 M, 6 F | Stimulation type: rTMS figure-of-8 coil; Stimulation parameters:; Condition 1: frequency 10 Hz; coil orientation not specified; 90% RMT; number of trains 5; duration of trains 10 s; ITI 50 s; total number of pulses 500; Condition 2: frequency 5 Hz; coil orientation not specified; 90% RMT; number of trains 10; duration of trains 10 s; ITI 50 s; total number of pulses 500; Condition 3: frequency 1 Hz; coil orientation not specified; 90% RMT; number of trains 1; duration of trains 500 s; total number of pulses 500; Condition 4: sham, coil angled 45º from scalp with synchronised electrical scalp stimulations to mask sensation; Stimulation location: M1 over the representation of the painful area; Number of treatments: 1 for each condition | Primary: VAS pain, anchors not specified; When taken: 0, 15, 30, 60, 90, and 180 minutes poststimulation; Secondary: none
Tzabazis 2013^37^ | Unclear, likely parallel RCT (for 1 Hz only), 10 Hz data open-label therefore excluded from this review | Country of study: USA; Setting: not reported, likely laboratory; Condition: fibromyalgia; Prior management details: “moderate to severe despite current and stable treatment regime”; n = unclear, abstract report (Schneider 2012 (see Tzabazis 2013)) stated 45, but full paper stated 16; Age mean (SD): 53.2 (8.9) years; Duration of symptoms, years mean (SD): not reported; Gender distribution: 14 F, 2 M | Stimulation type: rTMS 4-coil configuration; Stimulation parameters: frequency 1 Hz; no of trains not reported; duration of trains not reported; ITI not reported, intensity 110% RMT, total number of pulses per session 1800, stimulation duration 30 min; Stimulation location: targeted to the anterior cingulate cortex; Number of treatments: 20, x 1 daily (working days) for 4 wks; Control type: sham coil | Primary: BPI average pain last 24 h, NRS, anchors not reported; When taken: end of treatment, 4 wks post-treatment; Secondary: FIQ
Short 2011^38^ | Parallel RCT | Country of study: USA; Setting: laboratory; Condition: fibromyalgia; Prior management details: naive to TMS; n = 20; Age mean (SD): active group 54.2 (8.28) years, sham group 51.67 (18.19) years; Duration of symptoms, years mean (SD): active group 12.1 (7.75), sham group 10.10 (12.81); Gender distribution: 84% F | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation parasagittal, number of trains 80; duration of trains 5 s; ITI 10 s, intensity 120% RMT, total number of pulses per session 4000; Stimulation location: L DLPFC; Number of treatments: 10, x 1 daily (working days) for 2 wks; Control type: sham coil | Primary: pain VAS; 0 = “no pain”, 10 = “worst pain”; When taken: after 1 and 2 wks of treatment, then 1 wk and 2 wks posttreatment; Secondary: FIQ, BPI function scale
Tekin 2014^39^ | Parallel RCT | Country of study: Turkey; Setting: Rehabilitation outpatient unit; Condition: fibromyalgia; Prior management details: no analgesic use for 1 month prior to enrolment; n = 51; Age mean (SD): active group 42.4 (78.63) years, sham group 46.5 (8.36) years; Duration of symptoms: mean (SD) active group 10.81 (6.31) years, sham group 13.33 (6.65); Gender distribution: 47 F, 4 M | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation 45° angle from the midline, 100% RMT number of trains 30; duration of trains 5 s; ITI 12 s; total number of pulses 1500; Stimulation location: M1 midline, no neuronavigation; Number of treatments: 10 sessions daily - unclear whether only work days; Control type: sham coil - same sound and appearance, no control for sensory cues | Primary: pain NRS anchors 0 = no pain, 10 = most severe pain; When taken: end of intervention; Secondary: WHQoL-BREF
Umezaki 2016^40^ | Parallel RCT | Country of study: USA; Setting: not reported; Condition: burning mouth syndrome Prior management details: not reported; n = 26; Age mean (SD): active group 63.36 (10.78) years, sham group 64.42 (8.35) years; Duration of symptoms, mean (SD): active group 61.57 (32.10) months, sham group 65.58 (55.52); Gender distribution: active group 93% F, sham group 92% F | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation not specified, 100% RMT, number of trains 10; duration of trains 5 s; ITI 10 s; total number of pulses 3000; Stimulation location: L DLPFC; Number of treatments: 10 x 1 daily on work days; Control type: sham coil - same sound and appearance and sensory cues | Primary: pain NRS anchors 0 = no pain, 10 = extreme amount; When taken: end of stimulation and 15, 30, 60 days after start of treatment; Secondary: AEs
Yagci 2014^41^ | Parallel RCT | Country of study: Turkey; Setting: not reported; Condition: fibromyalgia; Prior management details: no improvement in cases of using medical treatment for fibromyalgia for at least 3 months; n = 28; Age mean (SD): active group 45.25 (9.33) years, sham group 43 (7.63) years; Duration of symptoms, mean(SD): active group 53 (29.15) months, sham group 54.92 (30.44); Gender distribution: all F | Stimulation type: rTMS; Stimulation parameters: frequency 1 Hz; coil orientation not reported, 90% RMT, number of trains 20; duration of trains 60 s; ITI 45 s; total number of pulses 1200; Stimulation location: L M1, no neuronavigation; Number of treatments: 10 sessions, wkdays for 2 wks; Control type: sham coil - same sound and appearance, no control for sensory cues | Primary: pain NRS anchors 0 = no pain, 10 = maximum pain imaginable; When taken: end of intervention, 1 month, 3 months; Secondary: FIQ, AEs
Yilmaz 2014^42^ | Parallel RCT | Country of study: Turkey; Setting: rehabilitation unit; Condition: post-SCI below lesion neuropathic pain; Prior management details: pain that is resistant to pharmacological (anticonvulsants, antidepressants, narcotics) and interventional treatments; n = 17; Age mean (SD): active group: 40 (5.1) years, sham group 36.94 (8) years; Duration of symptoms mean (SD): active group 32.3 (25.9) months, sham group 35.4 (17.9); Gender distribution: all M | Stimulation type: rTMS; Stimulation parameters: frequency 10 Hz; coil orientation handle pointing posteriorly, number of trains 30; duration of trains 5 s; ITI 25 s; total number of pulses 1500; Stimulation location: M1 midline; Number of treatments: daily for 10 wkdays; Control type: coil angled away - same sound and appearance, did not control for visual or sensory cues | Primary: pain NRS anchors 0 = no pain, 10 = worst pain imaginable; When taken: end of intervention, 6 wks, 6 months postintervention; Secondary: none relevant

Visual analogue scale (VAS), Numeric rating scale (NRS), Leeds assessment of neuropathic symptoms and signs (LANSS), World Health Organization Quality of Life – BREF (WHQoL-BREF), rTMS (repetitive transcranial magnetic stimulation), Brief pain inventory (BPI), Fibromyalgia Impact Questionnaire (FIQ), rTMS (repetitive transcranial magnetic stimulation), Resting motor threshold (RMT), Hz (Hertz), Dorsolateral prefrontal cortex (DLPFC), Adverse events (AE)

### APPENDIX E ONGOING STUDIES

#### Opioid Use Disorder

NCT Number | Title | Status | Conditions | Interventions | Completion Date
NCT03653169 | Use of Transcranial Magnetic Stimulation to Reduce Craving for Individuals With Opioid Use Disorder Taking Buprenorphine | Enrolling by invitation | Opioid-use Disorder | TMS | 7/1/2020
NCT04231708 | Effects of Pharmacological Stress and rTMS on Executive Function in Opioid Use Disorder | Not yet recruiting | Opioid Use Disorder | rTMS + pharmacotherapy | 12/31/2022
NCT04181515 | Using rTMS to Explore Neural Mechanisms of Stress-Induced Opioid Use | Not yet recruiting | Opioid-use Disorder | rTMS + pharmacotherapy | 6/1/2025
NCT04336293 | sTMS for Substance Use-disordered Veterans | Not yet recruiting | Opioid Addiction | sTMS | 5/31/2022
NCT03821337 | Transcranial Magnetic Stimulation (rTMS) as a Tool to Decrease Pain and Improve Functioning | Active, not recruiting | Opioid Use Disorder | rTMS | 5/31/2021
NCT03653169 | Use of Transcranial Magnetic Stimulation to Reduce Craving for Individuals With Opioid Use Disorder Taking Buprenorphine | Enrolling by invitation | Opioid Use Disorder | TMS | 7/1/2020
NCT04231708 | Effects of Pharmacological Stress and rTMS on Executive Function in Opioid Use Disorder | Not yet recruiting | Opioid Use Disorder | rTMS + pharmacotherapy | 12/31/2022
NCT04181515 | Using rTMS to Explore Neural Mechanisms of Stress-Induced Opioid Use | Not yet recruiting | Opioid-use Disorder | rTMS + pharmacotherapy | 6/1/2025
NCT04336293 | sTMS for Substance Use-disordered Veterans | Not yet recruiting | Opioid Addiction | sTMS | 5/31/2022
NCT03804619 | Accelerated Intermittent Theta-Burst Stimulation for Opiate Use Disorder | Not yet recruiting | Opiate Dependence, Depression | rTMS (theta burst) | 12/1/2022
NCT04432493 | Using Combined EEG and Non-invasive Brain Stimulation to Examine and Improve Reward Functioning in Opioid Use Disorder | Recruiting | Opioid-use Disorder | rTMS | 3/31/2022
NCT04157062 | An Open-Label Trial of Repetitive Transcranial Magnetic Stimulation for Opioid Use Disorder | Recruiting | Opioid-use Disorder | rTMS | 10/1/2021
NCT03229642 | Repetitive Transcranial Magnetic Stimulation in Patients With Opioid Use Disorders | Recruiting | Opioid Dependence | rTMS | 7/31/2020
NCT03538444 | Repetitive Transcranial Magnetic Stimulation for Opiate Use Disorder | Recruiting | Opiate Dependence, Chronic Pain | rTMS | 6/1/2021

#### PTSD

NCT Number | Title | Status | Conditions | Interventions | Completion Date
NCT01806168 | rTMS in the Treatment of PTSD | Active, not recruiting | PTSD | rTMS | 3/1/2019
NCT02158663 | Study Testing if Fast or Slow rTMS is Better for the Treatment of Posttraumatic Stress Disorder (PTSD) | Completed | PTSD/Depression | rTMS | 3/14/2019
NCT02584894 | Potentiation of Trauma Exposure in Post-traumatic Stress Disorder by Repeated Transcranial Magnetic Stimulation | Completed | PTSD | rTMS | 4/17/2020
NCT03932773 | Multi-site Confirmatory Efficacy Treatment Trial of Combat-related PTSD | Recruiting | PTSD | rTMS + cognitive processing therapy | 7/31/2023
NCT03114891 | Accelerated TMS to a Novel Brain Target in MDD and PTSD | Recruiting | PTSD/Depression | rTMS (theta burst) | 5/1/2021
NCT04325087 | Reduction of Trauma-induced Intrusions and Amygdala Hyperreactivity Via Non-invasive Brain Stimulation | Recruiting | PTSD | rTMS (theta burst) | 5/30/2020
NCT00134446 | Transcranial Magnetic Stimulation for Post-Traumatic Stress Disorder | Unknown status | PTSD | TMS

#### Traumatic Brain Injury (TBI)

NCT Number | Title | Status | Conditions | Interventions | Completion Date
NCT03819608 | Neuromodulation and Neurorehabilitation for mTBI Plus PTSD | Recruiting | mTBI/PTSD | rTMS | 3/1/2024
NCT03523507 | fMRI-neuronavigated rTMS Treatment for Symptoms of Depression Associated With Concussive TBI in the Military Population | Recruiting | TBI/Depression | rTMS | 2/1/2022
NCT02458521 | Transcranial Magnetic Stimulation (TMS) to Treat mTBI and PTSD | Unknown status | TBI/PTSD | rTMS | 5/1/2019

#### Pain

NCT Number | Title | Status | Conditions | Interventions | Completion Date
NCT03576781 | Developing rTMS Treatment Strategies for Pain in Opiate Dependence | Completed | Chronic Pain, Opioid Dependence | rTMS (theta burst) | 11/12/2019
NCT03576781 | Developing rTMS Treatment Strategies for Pain in Opiate Dependence | Completed | Chronic Pain, Opioid Dependence | rTMS (theta burst) | 11/12/2019
NCT03994991 | Transcranial Magnetic Stimulation (TMS) for Thoracic Surgery | Not yet recruiting | Chronic Pain | TMS | 8/1/2022
NCT03984201 | Accelerated Theta Burst in Chronic Pain: A Biomarker Study | Not yet recruiting | Chronic Pain | rTMS (theta burst) | 8/1/2023
NCT04203199 | H-coil TMS to Reduce Pain: A Pilot Study Evaluating Relative Efficacy of the H1 vs H7 Coil | Not yet recruiting | Chronic Pain, Opioid Use | rTMS | 7/1/2022
NCT02687360 | Imaging the Effects of rTMS on Chronic Pain | Recruiting | Chronic Pain, Opioid Dependence | rTMS | 10/1/2021
NCT02572726 | An Exploration of the Neuroplasticity of Endogenous Analgesia in Health and Chronic Pain | Recruiting | Pain \| Fibromyalgia | rTMS | 12/1/2020
NCT03681769 | Developing Brain Stimulation as a Treatment for Chronic Pain in Opiate Dependent | Recruiting | Chronic Pain, Opiate Dependence | rTMS (theta burst) | 7/1/2021
NCT04283643 | Noninvasive Brain Stimulation for Pain Relief | Recruiting | Acute Pain, Chronic Pain | TMS | 4/1/2021
NCT02687360 | Imaging the Effects of rTMS on Chronic Pain | Recruiting | Chronic Pain, Opioid-use Disorder | rTMS | 10/1/2021
NCT04156802 | Project Relief: Developing Brain Stimulation as a Treatment for Chronic Pain | Recruiting | Chronic Pain, Opioid Use | rTMS (theta burst) | 12/1/2021
NCT03973788 | Effects of Repetitive Transcranial Magnetic Stimulation on Pain Thresholds in Patients With Chronic Low Back Pain | Recruiting | Low Back Pain | rTMS | 8/31/2020
NCT03076294 | Repetitive Transcranial Magnetic Stimulation Associated With Manual Therapy in Knee Osteoarthritis Pain | Unknown status | Pain, Knee Osteoarthritis | TMS | 3/1/2019

#### Alcohol Use Disorder

NCT Number | Title | Status | Condition | Intervention | Completion Date
NCT03995173 | Pilot rTMS for AUD+mTBI | Recruiting | Alcohol Use Disorder, mTBI, PTSD | rTMS | 11/1/2020
NCT04043442 | rTMS Target Identification for Functional Disability in AUD+mTBI | Recruiting | Alcohol Use Disorder, mTBI | rTMS | 9/30/2023

### APPENDIX F DATA ABSTRACTION

#### CONTROLLED STUDIES

##### Pain

Author; Year; Study Design; N | Population; Patient characteristics: Mean age | Intervention; Study Follow-up | Comparator | TMS Protocol:; Location; Frequency (Hz); Intensity (% RMT); Sessions | Symptom Improvement | Other Outcomes | Harms
Neurological
Ahmed 2020^1^; RCT; N=30 | Patients with a diagnosis of diabetic neuropathy (stages 2a or 2b); Age: 50.8; % male: 36.67; % white: NR | rTMS and aerobic training exercises 1 wk | Transcutaneous electrical nerve stimulation (TENS) and aerobic training exercises. | Location: Precentral motor cortex (hemisphere contralateral to pain); Frequency: 20 Hz; Intensity: 80-90% RMT; Sessions: 5 session (daily) | Decrease in pain severity at 1 wk from baseline (p<0.05) in both groups, but no differences between groups. | NR | NR
Andre-Obadia, 2018^43^; Randomized crossover trial; N=35 | Patients with upper limb or facial neuropathic pain for at least 1 year; Age: 18-80; % male: NR; % white: NR | rTMS; NR | Sham rTMS: sham coil mimicking sounds and vibrations | Location: Hand or facial motor cortex; Frequency: 20 Hz; Intensity: 90% RMT; Sessions: 3 sessions (2 active, 1 sham, separated by 2 wks) | rTMS targeted over the hand motor cortex had greater pain relief than rTMS targeted over facial cortex face rTMS (p=0.002) and sham (p=0.005). | NR | NR
Galhardoni 2019^44^; RCT; N=100 | Patients with chronic (> 3 months) CNP due to stroke or spinal cord lesions; Age: 55.02; % male: NR; % white: NR | Deep TMS 12 wks | Sham deep TMS: coil mimicking sounds and vibrations | Location: Anterior cingulate cortex (ACC) or posterior superior insula (PSI); Frequency: 10 Hz; Intensity: 90% RMT; Sessions: 16 sessions (daily for 5 days (induction) then 1 session/wk for 11 wks) | NRS score was not significantly different between groups at any point during the study. | Active dTMS treatments had no significant effects on pain interference with daily activities (Brief Pain Inventory), or quality of life (SF-36). | Pain (mostly headaches) after each dTMS was the most prevalent adverse event
Hosomi, 2020^45^; RCT; N=144 | Adult patients with neuropathic pain for more than 6 months; Age: 61.9; % male: 64.6; % white: NR | rTMS; 5 wks | Sham rTMS: sham coil mimicking sounds and vibrations | Location: Primary motor cortex (M1) targeting part of the body with the worst pain; Frequency: 5 Hz; Intensity: 90% RMT; Sessions: 5 sessions (daily), then 1 session/wk for 4 wks (responders only - open-label) | Pain improvement not significantly different (p=0.58) between the rTMS (−8.0) and sham (−9.2) during the daily sessions. No difference in number of responders (≥ 10mm decrease VAS) between rTMS (31%) and sham (37%). The patients enrolled in the continuous wkly rTMS achieved more pain relief in with rTMS compared with the sham (p<0.01). | No difference in quality of life scores over time or between groups. | No serious adverse events were observed
Kim, 2020^46^; RCT; N=30 | Patients with CNP; Age: 61.9; % male: 64.6; % white: NR | Intermittent theta-burst stimulation (iTBS) 5 days | ham iTBS: coil turned away from skull at 90° | Location: Ipsilateral hemisphere; Frequency: 50 Hz; Intensity: 80% RMT; Sessions: 5 sessions (daily) | S-LANSS decreased more in iTBS (−4.53) vs sham (−0.8) (p=0.002). NRS decreased more in iTBS (−2.13) vs sham (−0.86) (p=0.029). | NR | No adverse events were reported
Quesada, 2020^47^; Randomized crossover trial; N=42 | Adult patients with medically refractory chronic CNP for at least 6 months; Age: 62.8; % male: 63.3; % white: NR | rTMS; 7 months | sham rTMS | Location: Primary motor cortex contralateral to the patient’s pain; Frequency: 20 Hz; Intensity: 80% RMT; Sessions: 8 sessions (4 sessions each stimulation) over 9 wks (3 wks between sessions and 8 wk washout) | Percent of pain relief (%R) was greater after rTMS phase (33.8%) compared to sham phase (13%). 54% (rTMS) vs 21% (sham) achieved ≥30% pain relief and 35% (rTMS) vs 12% (sham) achieved ≥50% pain relief. Significant decrease in VAS after rTMS phase but not sham phase. | Quality of life (EQ5-D) did not change over time or between groups. | One patient left due to pain exacerbation during both active rTMS and sham.
Sun, 2019^48^; RCT; N=21 | Right-handed inpatient rehab patients with neuropathic pain following SCI; % male: 88; % white: NR | rTMS; 6 wks | Sham rTMS: coil turned away from skull at 90° | Location: Left primary motor cortex; Frequency: 10 Hz; Intensity: 80% RMT; Sessions: Daily sessions for 6 wks, with one-day interval per wk | Pain intensity decreased from baseline to 6 wks in rTMS group (5 vs 1.5* NRS) and sham group (4.5 vs 3* NRS). Pain intensity decreased more in rTMS group compared to sham and the difference became significant at wk 2. *Estimated from Figure 4 | NR | No patients complained of discomfort during or after treatment and no pathologic effects were reported.
Complex Regional Pain
Gaertner, 2018^49^; Cohort; N=21 | People who met “Budapest” Clinical Diagnostic Criteria for CRPS and had pain greater than 3/10 average on a numerical rating scale (NRS).; Age: 44; % male: 9.5; % white: NR | iTBS followed by TMS; 2 wks | 1 TMS session group vs 5 TMS session group | Location: targeted over motor cortex to stimulate CPRS affected region; Frequency: 50 Hz (iTBS) then 10 Hz; Intensity: 70% (iTBS) then 80%; Sessions: 1 or 5 sessions over 5 days | Both groups demonstrated significant pain reduction after 1 wk posttreatment; but no differences between groups.; Treatment response (≥30% reduction in pain from baseline): 60% of participants with 1 session responded at wk 1. 58% and 50% of participants responded at wks 1 and 2 with 5 sessions. | NR | One subject withdrew due to adverse head pain. No serious adverse events occurred. Headache and nausea were the most common side effects.
Fibromyalgia
Abd Elghany, 2019^50^; Non-randomized controlled trial; N=120 | Outpatients with FMS according to ACR 2010 diagnostic criteria; Age: NR; % male: 0 (all female); % white: NR | rTMS; One month | Regenerative injection therapy (RIT) (3 injections, 2 wks apart) | Location: DLPFC; Frequency: 10 Hz; Intensity: NR; Sessions: 15 sessions (every other day for 1 month) | Significant decrease in mean VAS score with rTMS immediately after treatment (−20) and at 1 month (−24.3) and with injection therapy immediately after treatment (−25.2) and at 1 month (−49). Injection therapy had lower pain scores at baseline (p=0.002) and 1 month compared to rTMS (p<0.001). | Significant decrease in mean Fibromyalgia Impact Questionnaire Revised (FIQR) score with rTMS (−7.29) and injection therapy (−30.7) at 1 month. Injection therapy had lower FIQR scores at 1 month compared to rTMS (p<0.001). | NR
Atlas, 2019^51^; RCT; N=30 | Right-handed, female patients with FMS according to ACR 2010 Diagnostic Criteria; Age: 50; % male: 26.3; % white: NR | rTMS; 3 wks | Sham rTMS: reverse position coil at 0.1 Hz, 1% RMT | Location: left primary motor cortex (M1) or Left DLPFC; Frequency: 10 Hz; Intensity: 90% RMT; Sessions: 15 sessions (sessions/wk for 3 wks) | Significant improvements from baseline in VAS score in M1 (−2.8), DLPFC (−2.2) and sham (−1.7). Decrease in VAS significantly greater in Group M1 vs sham (p=0.028), but not DLPFC vs sham (p=.238) or M1 vs DLPFC (p=0.237) | Significant improvements from baseline in FIQ score in M1 (−14.7), DLPFC (−12.3) and sham (−12.4). No differences in decrease in FIQ amongst groups. Significant improvements from baseline in SF-36 physical functioning score in M1 (25), DLPFC (19.5) and sham (4). SF-36 physical functioning improvement greater in M1 vs sham (p=0.002), and DLPFC vs sham (p=.004), but not M1 vs DLPFC (p=0.62 | No adverse events
Bilir, 2020^52^; RCT; N=20 | Adult patients with diagnosis of FMS according to 2016 Fibromyalgia diagnostic criteria; Age: 45.25; % male: 0; % white: NR | rTMS; 6 wks | Sham rTMS: reverse position coil at 1% RMT | Location: Left DLPFC; Frequency: 10 Hz; Intensity: 90% RMT; Sessions: 14 sessions (5 days/wk for 2 wks (induction phase), then 1 session/wk for 4 wks) | There was no significant difference in VAS-pain over time or between groups (p>0.05). | FIQ decreased at wk 2 vs baseline in rTMS group but not sham group. No differences compared to baseline at wk 6 in either group. No differences at any time between groups | No adverse events were reported
Cheng, 2019^53^; RCT; N=20 | Patients with FMS according to ACR-2010 diagnostic criteria and DSM-IV MDD; Age: 50; % male: 26.3; % white: NR | rTMS; 2 wks | Sham rTMS: sham coil mimicking sounds and vibrations | Location: Left DLPFC; Frequency: 10 Hz; Intensity: 100% RMT; Sessions: 10 sessions (5 sessions/wk for 2 wks) | Decrease in pain score (VAS) with rTMS (wk 2 vs wk 1, −0.7, p=0.021), but not with sham (wk 2 vs wk 1, +0.1, p=0.585). No significant difference between groups at wk 1 (p=0.975) or wk 2 (p=0.950) | NR | One participant complained of mild dizziness with no other adverse events reported.
Fitzgibbon, 2018^54^; RCT; N=26 | Patients with FMS according to ACR-2010 diagnostic criteria; Age: 45.6; % male: 8.3; % white: NR | rTMS; 1 month | Sham rTMS: sham coil mimicking sounds and vibrations | Location: Left DLPFC; Frequency: 10 Hz; Intensity: 120% (RMT); Sessions: 20 sessions (5 consecutive session/wk for 4 wks) | Pain improved at 1 month vs baseline in both rTMS and sham groups on all pain measures. No significant differences between groups was observed. rTMS group significantly more likely to respond (achieve a minimum 30% improvement in pain intensity ratings) 7 rTMS vs 1 sham (p=0.024). | Both groups improved at 1 month vs baseline on FIQ, no differences between groups were observed. | 5 participants reported site discomfort, 7 reported headaches, 2 reported neck pain, 3 reported nausea, 1 reported dizziness, and 2 reported other adverse events
Guinot, 2019^55^; RCT; N=39 | Patients with FMS according to ACR-2010 diagnostic criteria; Age: 44.6; % male: 8.9; % white: NR | rTMS; 6 months | Sham rTMS (sham coil mimicking sounds and vibrations) + multicomponent therapy (aerobic, strength, relaxation training) | Location: Left DLPFC; Frequency: 10 Hz; Intensity: 90% RMT; Sessions: 14 sessions (5 days/wk for 2 wks (induction phase), then 1 session/wk for 4 wks) | There was no significant difference in VAS-pain over time or between groups (p>0.05). | FIQ improved after therapy (wk 14) and at 6 month follow-up for both rTMS and sham groups (p<0.001). No differences in pain reduction between groups | No adverse effects were recorded during the study
Headache
Mattoo, 2019^56^; RCT; N=30 | Right-handed CTTH patients with history of headache >15 days a month for 3 months or more; Age: 35.7; % male: NR; % white: NR | rTMS 4 Wks after completion | sham rTMS: coil placed perpendicular to right DLPFC | Location: Right DLPFC; Frequency: NR; Intensity: 110% RMT; Sessions: 20 sessions (5 sessions/wk for 4 wks) | NRS score decreased significantly (P<0.001) in the rTMS group compared to placebo. | rTMS group improved significantly more than sham group in Headache Impact Test-6 (HIT-6) (p<0.001), but not WHO QOL score | NR
Sahu, 2019^57^; RCT; N=41 | Right-handed patients with a diagnosis of migraine with or without aura according to the international Classification of Headache Disorders-II | Intermittent theta-burst stimulation (iTBS); 12 Wks | sham iTBS: coil placed perpendicular to left DLPFC | Location: Left DLPFC; Frequency: 50 Hz; Intensity: 80; Sessions: 10 session (2x/day for 5 days) | There was a greater decrease in frequency, duration, and severity of migraine in the active group compared to the sham group over the study period (p<0.001). | There was a greater decrease in MIDAS score compared to sham group over the study period (p<0.001). | There were no significant adverse effects observed during the entire period of study

Abbreviations: rTMS, (Repetitive Trancranial Magnetic Stimulation), Dorsolateral prefrontal cortex (DLPFC), World Health Organization Quality of Life assessment (WHO QOL), Migraine Disability Assessment Score (MIDAS), Chronic tension-type headache (CTTH), Fibromyalgia Impact Questionnaire (FIQ), Numerical rating scale (NRS), Resting motor threshold (RMT), Hertz (Hz)

##### PTSD

Author; Year; Study Design; N | Population; Patient characteristics: Mean age | Intervention; Study Follow-up | Comparator | TMS Protocol:; Location; Frequency (Hz); Intensity (% RMT); Sessions | Symptom Improvement | Other Outcomes | Harms
Ahmadizadeh, 2018^58^; RCT; N=65 | Veterans with current combat-related PTSD symptoms; Age: 50.45; % male: 100; % white: NR | rTMS; 4 wks | Sham rTMS: sham coil mimicking sounds and vibrations | Location: bilateral (left and right) or right DLPFC; Frequency: 20 Hz; Intensity: 100 % RMT; Sessions: 10 session (3 sessions/wk for 2 wks; 2 sessions/wk for 2 wks) | Greater proportion of responders (≥ 2 std from mean PCL) in rTMS (bilateral (62.5%) and unilateral (41.2%)) groups compared to sham (0%) (p=0.0001) and no difference was found between bilateral and unilateral groups. Significant mean improvement in PCL in unilateral and bilateral rTMS vs sham after all sessions. | NR | 2 patients withdrew due to headache and 1 patient withdrew due to discomfort (both patients in bilateral rTMS group).
Fryml, 2019^59^; RCT; N=8 | Veterans (OIF/OEF) with combat-related PTSD; Age: 28.1; % male: 87.5; % white: NR | rTMS and Prolonged exposure therapy (PE); 8 wks | Sham rTMS (details NR) | Location: Right or left prefrontal cortex; Frequency: 10 Hz; Intensity: 120% RMT; Sessions: 8 (1 session/wk for 8 wks) | Reduction in CAPS scores was 55% (90% CI 18.5-53.5) with rTMS compared to 40% (90% CI 13.6-73.0) with sham at session 5. | NR | No adverse events or serious adverse events occurred during the study.
Isserles, 2013^60^; RCT; N=30 | Veterans with PTSD; Age: 43.4; % male: 76.9; % white: NR | deep TMS + traumatic or positive imagery; 4 wks | Sham deep TMS + traumatic imagery | Location: Prefrontal cortex; Frequency: 20 Hz; Intensity: 120%; Sessions: 12 sessions (3 sessions/wk for 4 wks) | CAPS score improved significantly in rTMS + trauma imagery group (−27, p<.0.05), but not in rTMS + positive imagery group (−10, p>.0.05), or sham group (−10, p>0.05) | NR | A few patients had mild headaches
Kozel, 2018^61^; RCT; N=103 | Veterans deployed to combat regions, 2001-present; Age: NR (range 18-60); % male | rTMS + cognitive processing therapy | sham rTMS (inactive coil) + cognitive processing therapy | Location: right DLPFC; Frequency: 1 Hz; Intensity: 110% motor threshold; Sessions: 12 sessions (1session/wk for 12 wks) | Total CAPS score had a greater decrease from baseline in rTMS (−48) compared to sham (−36) group (p<0.023) | NR | 3 participants withdrew due to headaches (2 rTMS, 1 sham rTMS)
Kozel, 2019^62^; RCT; N=35 | Veterans suffering from PTSD with and without depressive symptoms | rTMS; 3 months | 10 Hz. vs 1 Hz; rTMS | Location: Right DLPCF; Frequency: 1 Hz or 10 Hz; Intensity: 110% RMT; Sessions: 36 sessions (timing NR) | CAPS response: 29% 1 Hz vs 31% 10 Hz (p=1.0) after 30 sessions; CAPS remission: 21% 1 Hz. vs 33% 10 Hz (p=0.67) after 30 sessions; Improved CAPS score with 1 Hz (−9.4) and `0 Hz (−10.9) rTMS after 30 sessions. No significant difference between groups. | No difference in Inventory of Psychosocial Functioning (IPF) score with 1 Hz (-.4) or 10 Hz (−0.5) rTMS after 30 sessions | There were no seizures and no continuing complications. Two participants could not tolerate treatment at the first visit (10 Hz group)
Leong, 2020^63^; RCT; N=31 | Civilians with non-combat related PTSD (most common type of trauma was sexual violence 52%); Age: 43,7; % male: 17.1; % white: NR | rTMS; 3 months | sham rTMS: sham coil (1 Hz or 10 Hz) mimicking sounds | Location: Right DLPFC; Frequency: 1 Hz or 10 Hz; Intensity: 120% RMT; Sessions: 10 sessions (5 sessions/wk for 2 wks) | PTSD symptoms improved at the end of treatment with 1 Hz rTMS (p=0.021) compared to sham, but not with 10 Hz rTMS (p=.065) compared to sham. There was a significant time x treatment effect over the 3 month follow-up (p=0.046). | NR | On participant withdrew due to suicidal ideation.
Nam, 2013^64^; RCT; N=18 | Patients with non-military related PTSD; Age: 34.3; % male: 37.5; % white: NR | rTMS; 8 wks | Sham rTMS: coil turned away from skull at 90° | Location: right prefrontal cortex; Frequency: 1 Hz; Intensity: 100% RMT; Sessions: 15 sessions (5 consecutive sessions/wk for 3 wks) | PTSD symptoms (CAPS-total) improved for all groups (p<0.001) but no significant effect of treatment group (p=0.147). Significant effect of time x treatment (p=0.008). | NR | Mild adverse effects, such as headache (3 rTMS, 2 sham), dizziness (1 rTMS, 1 sham), and difficulty concentrating (1 sham)
Petrosino, 2020*^65^; RCT; N=46 | Veterans with PTSD | Intermittent theta-burst stimulation (iTBS) | sham iTBS (details NR) | Location: right DLPFC; Frequency: 50 Hz; Intensity: 80% RMT; Sessions: 10 sessions (5 consecutive sessions/wk for 2 wks) | Overall, 47.8% of patients had clinical relapse (1 patient (2.1%) overdose death, 3 patients (6.5%) inpatient hospitalization, and 18 patients (39.1%) TMS retreatment). Fewer patients in active iTBS group (33.3%) had relapse compared to sham (63.6%) (OR relapse = 3.5, 95% CI 1.04 to 11.79). | NR | NA
Philip, 2019^66^; RCT; N=23 | People with PTSD and MDD; Age: 51; % male: 84.8; %: 88; % white: NR | Synchronized TMS (sTMS) (rotating magnets synchronized to individuals intrinsic alpha frequency (IAF)) | Sham sTMS: sham device with no rotating magnets; 1 year | Location: NR; Frequency: NR; Intensity: NR; Sessions: 20 (5 sessions/wk for 4 wks) | All participants demonstrated significant reductions in PTSD and MDD symptoms (p< 0.001). No significant difference in PTSD symptoms (PCL total score) (p=0.083) or MDD symptoms (QIDS-SR total score) (p=0.091) between groups, but greater improvement in “PTSD threshold symptoms” in sTMS group (p=0.011). | NR | 2 participants (sTMS)reported headaches, and 1 participant (sTMS) reported nausea
Philip, 2019^67^ (iTBS)*; RCT; N=50 | Veterans with PTSD (90% with comorbid depression); Age: 50.5; % male: 84; % white: 84 | Intermittent theta-burst stimulation (iTBS); 1 month | Sham iTBS (details NR) | Location: right DLPFC; Frequency: 50 Hz; Intensity: 80% RMT; Sessions: 10 sessions (5 consecutive sessions/wk for 2 wks) | No difference in PTSD symptoms (CAPS) between groups (p=0.31) after treatment (2 wks). At 1 month (after unblinded phase) iTBS had greater PTSD symptom improvement compared to sham (p<0.001). More patients responded (≥ 12 point CAPS reductions) with iTBS (81%) compared to sham (67%) (p<0.001). | Statistically significant improvement on Social and Occupational Functioning Assessment Scale (SOF) (p=0.04) after 2 wks of iTBS compared to sham. | NR
Watts, 2012^68^; RCT; N=20 | People with PTSD; Age: 55.9; % male: 90; % white: 100 | rTMS; 10 wks | Sham rTMS: sham coil mimicking sounds and vibrations | Location: Right DLPFC; Frequency: 1 Hz; Intensity: 90% RMT; Sessions: 10 sessions (5 consecutive days/wk for 2 wks) | rTMS group had significant reduction in PTSD symptoms compared with sham after treatment (2 wks) (p=0.009 CAPS, p=0.002 PCL). CAPS scores remained significantly improved from baseline at 2 months post-treatment, but 6/10 participants had ≥ 10 point worsening in PTSD symptoms from post-treatment to 2 months). | NR | NR

Abbreviations: Post-traumatic stress disorder (PTSD), PTSD checklist-military version (PCL-M), Clinician Administered PTSD Scale (CAPS), PTSD Checklist (PCL), rTMS (repetitive Transcranial Magnetic Stimulation), Intermittent theta-burst stimulation (iTBS), Dorsolateral Prefrontal Cortex (DLPFC), Resting motor threshold (RMT), Operation Iraqi Freedom / Operation Enduring Freedom (OIF/OEF), Migraine Disability Assessment Score (MIDAS), Adverse events(AE)

##### TBI

Author; Year; Study Design; N | Population; Patient characteristics:; Mean age | Intervention; Study Follow-up | Comparator | TMS Protocol:; Location; Frequency (Hz); Intensity (% RMT); Sessions | Symptom Improvement | Other Outcomes | Harms
Choi 2018^69^; RCT; N=12 | Adults with mild TBI and pain lasting at least 6 months; Age: 42.6; % male: 50; % white: NR | rTMS; 6 wks | Sham rTMS: coil turned away from skull at 90° | Location: Primary motor cortex; Frequency: 10 Hz; Intensity: 90% RMT; Sessions: 10 sessions (5 per wk for 2 wks) | Changes in NRS over time were significantly different between groups (p<0.001). NRS score significantly lower in rTMS group compared to sham group at each follow-up point. | SF-36 physical component scores increased more in rTMS group compared to sham group at each time point, but SF-36 mental component scores did not change significantly over time. | No adverse events reported during study.
Hoy, 2019^70^; RCT; N=21 | People with TBI (≥ 6 wks post TBI) experiencing current moderate severity depressive episode; Age: 46.3; % male: 47.6; % white: NR | rTMS; 4 wks | Sham treatment: coil turned away at 45° | Location: Left or right DLPFC; Frequency: 1 Hz (right), 10 Hz (left); Intensity: 110% RMT; Sessions: 20 sessions (over 4 wks) | Significant improvement in depressive symptoms (MADRS) for both groups (p=0.002), but no differences between groups. | Improvement in Trail Making Test (B) with rTMS, but no difference between groups. | More patients reported side effects with rTMS compared to sham (72% vs 30%), but statistically insignificant (p=0.146).
Lee, 2018^71^; RCT; N=13 | Patients with TBI (≥ 6 months) without severe depression; Age: 41.9; % male: 69; % white: NR | rTMS + neurodevelopmental therapy; 2 wks | Sham treatment + neuro-developmental therapy | Location: Right DLPFC; Frequency: 1 Hz; Intensity: 100% RMT; Sessions: 10 sessions (5 consecutive sessions/wk for 2 wks) | Significant improvements in depressive symptoms after rTMS (p<0.05) but not after sham. Improvement with rTMS vs sham: MADRS (−6.86 vs −0.34), | Improvement in function after rTMS but not after sham. Improvement with rTMS vs sham: TMT (−6.03 vs −1.20), and SCWT (−19.99 vs −3.00). | No adverse effects reported.
Leung, 2016^72^; RCT; N=24 | Veterans with mild traumatic brain injury (MBTI) and post-traumatic headache; Age: 41; % male: 87.5; % white: NR | rTMS (targeted by neuronavigated TMS); 4 wks | Sham treatment: coil turned away at 180° | Location: Left motor cortex; Frequency: 10 Hz; Intensity: 80% RMT; Sessions: 3 sessions (within 1 wk) | More patients in rTMS group had ≥ 50% headache reduction compared to sham (58.3% vs 16.6%, p=0.035). Composite score of debilitating headache exacerbation significantly reduced in rTMS group at 4 wks while sham did not. | No difference in Conner’s Continuous Performance (CPT) at wks 1 or 4 between groups. Significant interaction of visit and treatment at 1 wk, with an increase in CPT score with rTMS, but decrease in CPT score with sham. | One patient (rTMS) reported local tenderness at treatment site. Two subjects (one from each group) reported mild transient dizziness
Leung, 2018^73^; RCT; N=29 | Veterans with mild traumatic brain injury related headache (MTBI-HA); Age: 34.1; % male: 79.3; % white: NR | rTMS (targeted by neuronavigated TMS); 4 wks | Sham treatment: coil turned away at 180° | Location: Left prefrontal cortex; Frequency: 10 Hz; Intensity: 80% RMT; Sessions: 4 sessions (within 1 wk) | Signification reduction (p<0.0001) in average daily persistent headache intensity with rTMS but not sham at 1-wk (−25.3% vs −<1%) and 4-wks (−23% vs −2.3%). Significant reduction (p=0.009) in % of patients no longer experiencing persistent headaches with rTMS but not sham at 1-wk (50% vs 7%) and 4-wks (57% vs 29%). | No overall interaction between group and time on Conner’s Continuous Performance (CPT). | No side effects reported.
Manko, 2013^74^; Non-randomized controlled trial; N=40 | People with severe TBI and prolonged coma undergoing long-term rehab; Age: NR; % male: NR; % w white: NR | rTMS; NR | Relative beta training - biofeedback and neurofeedback | Location: NR; Frequency: NR; Intensity: NR; Sessions: NR | Mental and physical comfort significantly improved with rTMS (p<0.001) but not in control group (p=.0797). | NR | NR
Neville, 2019^75^; RCT; N=36 | People with chronic (>12 months post-injury) TBI; Age: 31.1; % male: 90; % white: NR | rTMS; 90 days | Sham rTMS: sham coil mimicking sounds and vibrations | Location: Left DLPFC; Frequency: 10 Hz; Intensity: 110% RMT; Sessions: 10 sessions (daily) | No differences in executive function between groups or in time x group interactions. rTMS group improved significantly at 90-days compared to baseline (p<0.05). | NR | Greater frequency of mild adverse events with rTMS compared to sham (70.6% vs 46.2%).
Rao, 2019^76^; RCT; N=34 | People with TBI and major depressive disorder; Age: 40; % male: 53.3; % white: 63.3 | rTMS; 16 wks | Sham rTMS: sham coil mimicking sounds and vibrations | Location: Right DLPFC; Frequency: 1 Hz; Intensity: 110% RMT; Sessions: 20 session (5 consecutive sessions/wk for 4 wks) | No statistically significant differences between groups in changes in HAM-D scores or on rates of remission or response. HAM-D scores varied widely, favoring rTMS at some time points (8 and 16 wks) and sham at others (4 and 12 wks). | Effects on neuropsychological functioning varied and favored rTMS for some measures and sham for others. | Two participants withdrew (rTMS) due to headaches. Common side effects included headache, worsening mood, dizziness, discomfort at stimulation site, insomnia, other general effects. No difference between groups.
Siddiqi, 2019^77^; RCT; N=15 | People TBI and treatment-resistant depression; Age: 45.8; % male: 73.3; % white: NR | rTMS (targeted by resting-state network mapping) NR (study terminated for “logistical reasons”) | Sham rTMS: sham coil mimicking sounds and vibration | Location: Left and right DLPFC; Frequency: 1 Hz (right), 10 Hz (left); Intensity: 120% RMT; Sessions: 20 sessions (over 5 wks) | Mean MADRS improvement was greater with rTMS (56%) than with sham (27%). Hypothesis testing not completed due to study termination. | No clear differences in NIH Toolbox cognitive. Emotional composite scores. | No significant adverse events
Stilling, 2020^78^; RCT; N=20 | People with persistent post-traumatic headache and post-concussion symptoms after TBI; Age: 36; % male: 10; % white: NR | rTMS; 6 months | Sham rTMS: sham coil mimicking sounds and vibrations | Location: Left DLPFC; Frequency: 10 Hz; Intensity: 70 % RMT; Sessions: 10 sessions (5 consecutive sessions/wk for 2 wks) | Significant overall time effect for average headache severity (p=0.03) but no effect of treatment group at 1-month post-treatment. | Significant time effect for quality of life (Quality of Life after Brain Injury (QOLIBRI), p = 0.020). There were no significant interactions, time effects, or treatment effects for cognition. | Side effects reported included mild aggravation of headache, scalp discomfort, toothache, and dizziness. No serious adverse effects.

Abbreviations: Numerical Rating Scale (NRS), Montgomery Asberg Depression Rating Scale (MADRS), Trail Making Test (TMT), Stroop Word Color Test (SCWT), Hamilton Depression Rating Scale (HAM-D), Dorsolateral prefrontal cortex (DLPFC), rTMS (repetitive transcranial magnetic stimulation), Traumatic brain injury (TBI), Quality of Life after Brain Injury (QOLIBRI), Montreal Cognitive Assessment (MoCA), Conner’s Continuous Performance (CPT), Resting motor threshold (RMT), Hertz (Hz)

##### Opiate Addiction

Author; Year; Study Design; N | Population; Patient characteristics: Mean age | Intervention; Study Follow-up | Comparat or | TMS Protocol:; Location; Frequency (Hz); Intensity (% RMT); Sessions | Symptom Improvement | Other Outcomes | Harms
Liu, 2020^79^; RCT; N=118 | Male heroin use disorder patients referred to addiction rehabilitation centers; Age: 39; % male: 100; % white: NR | rTMS; 90 days | Wait list | Location: Left DLPFC; Frequency: 10 Hz or 1 Hz; Intensity: 100% RMT; Sessions: 20 sessions over 28 days | Craving scores decreased more in first 30 days in both 1 Hz (−25.3 points) and 10 Hz groups (−29 points), compared to control (−11.6 points). All groups had significantly reduced craving score at 30, 60, and 90 days compared to baseline. No group had significant change in craving score at 60 or 90 days compared to 30 days. | None | Mild side effects reported (dizziness, headache, neck pain, insomnia, etc). Six subjects discontinued treatment for insomnia and headache.
Shen, 2016^80^; RCT; N=20 | Heroin addicted adults; Age: range 30-54; % male: 100; % white: NR | rTMS; 5 days | Sham rTMS: coil turned away from skull at 90° | Location: Left DLPFC; Frequency: 10 Hz; Intensity: 100% RMT; Sessions: 5 sessions (daily) | Craving score reduction of 20 points (60 vs 40) from baseline after rTMS (p=0.015) and 0 points (62 vs 62) from baseline after sham rTMS (p>0.05). | None | No subject reported any side effects

Abbreviations: Repetitive transcranial magnetic stimulation (rTMS), Dorsolateral prefrontal cortex (DLPFC), Motor threshold (MT), Hertz (Hz), Resting motor threshold (RMT), Not reported (NR)

#### CASE SERIES

Author Year | Condition | Intervention; Study follow-up | Primary Outcome Measure | Symptom Improvement | Harms
Mrabet, 2019^81^; N=19 | Pain | rTMS; One wk | Pain intensity via verbal rating scale (VRS) | Statistically significant difference was observed in the VRS score before and after the rTMS sessions with a median decrease of 3 points in the intensity of pain | No serious side effects were noted and in particular no epileptic seizures were observed. Less than 1% of rTMS sessions produced headache.
Quesada, 2018^47^; N=80 | Pain: neuropathic | rTMS; One year | Percentage of pain relief (%R), duration of pain relief (DPR), numeric rating scale (NRS), neuropathic pain symptom inventory (NPSI), and pain relief score (PRS). | %R was 28% and DPR (11 days after the first 4 sessions. After 12 months of treatment (15 sessions) a cumulative effect on %R (48%), DPR (20 days). This effect reached significance after 4 sessions and was further maintained over 12 months. | No adverse events occurred
Lawson, 2018^82^; N=50 | Pain: Neuropathic | rTMS; 6 wks | Visual analogue scale (VAS) for pain intensity | 8/46 patients reported a significant level of pain relief (P < 0.001). | 31/48 patients in the cohort suffered from atypical facial pain
Hodaj, 2020^83^ N=57 | Pain: orofacial, neuralgia, neuropathic | rTMS; NR | VNS scores for pain, Analgesic effect, Neuropathic Pain Symptom Inventory (NPSI) | Analgesic response (pain intensity) decrease > 30% compared to baseline, observed in 39 patients (68%). | No serious adverse events reported
Pinot-Monange, 2019^84^; N=12 | Pain: pelvic pain | rTMS; 4 wks | Patient Global Impression of Change | 75% reported improvement on the Patient Global Impression of Change with a reduction in both pain intensity and pain interference | No serious adverse effects. 50% of patients reported light headaches and 25% described asthenia
Nikkola, 2020^85^; N=11 | Pain: pelvic pain | rTMS; 12 wks | Numerical rating scale (NRS) for pain relief | Decreased pain was observed on the NRS after treatment and at 1 and 8 wks (P=0.019, P=0.006, P=0.042, respectively). | Mild transient tension headache reported by 2 patients. No adverse events or increase in pain occurred
Carpenter, 2018^86^; N=40 | PTSD/MDD | rTMS; NR | PTSD Checklist (PCL) and Inventory of Depressive Symptomatology, Self-Report (IDS-SR) for PTSD and MDD symptoms. | Stimulation significantly reduced PTSD symptoms (PCL baseline mean ± SD score 52.2 ± 13.1 versus endpoint 34.0 ± 21.6; p<.001). MDD symptoms also improved significantly (IDSSR baseline 47.8 ± 11.9 to endpoint 30.9 ± 18.9; p<.001); 15 patients (42.9%) demonstrated categorical response and 12 (34.3%) remitted. | Four patients experienced serious adverse events; 3 required hospitalization for worsening symptoms with suicidality, and 1 for suicidality and substance abuse. One patient withdrew due to exacerbation of migraine. Fourteen (40%) experienced at least mild activation of PTSD symptoms; all but 1 of these was taking stimulants or bupropion.
Taghva, 2015^87^; N=16 | PTSD | EEG-guided magnetic resonance therapy; NR | PTSD checklist (PCL-M), | Clinical improvements on the PCL-M were seen in all 16 patients, with an average pre-treatment score of 54.9 and post-treatment score of 31.8 (P < 0.001). | No adverse events were reported
Oznur, 2014^88^; N=20 | PTSD/Depression | rTMS; NR | Impact of Event Scale (IES), Beck Depression Inventory, Beck Anxiety Inventory | Statistically significant decreases in IES hyperarousal scores (from 21.4+−4.7 to 19.0 +−4.2, p=0.02). No statistically significant differences between total IES scores, IES intrusion scores, IES avoidance scores, Beck Depression Inventory, and Beck Anxiety Inventory scores | NR
Woodside, 2017^89^; N=14 | PTSD/Eating disorders | rTMS; NR | PTSD checklist-Civilian (PCL-C) and Difficulties in Emotional Regulation Scale (DERS) | PCL-C scores reduced by 51.99% +−27.24% overall (p<0.001). DERS scores improved by 36.02% +−24.24% overall. | No adverse events aside from transient headaches during first treatments
Philip, 2016^90^; N=10 | PTSD/Depression | rTMS; NR | PTSD Checklist (PCL), Quick Inventory of Depressive Symptamatology (QIDS) | Significant reduction in PTSD symptoms (p=0.003, effect size=1.12) and depression symptoms (p=0.005, effect size=1.09). | No adverse events
Nursey, 2020^91^; N=8 | PTSD | Intermittent theta-burst stimulation; 3 months | Clinician-Administered PTSD Scale for DSM-5 (CAPS-5), Hamilton Depression Rating Scale (HAM-D) | Reductions in both PTSD (effect size= −1.78) and depression (effect size=−1.16) symptom severity post-treatment. Continued further modest decline at 3-month follow-up. | No serious adverse events aside from mild to moderate cranial pain and headaches
Seagly, 2016^92^; N=7 | PTSD | Low-frequency TMS; 1 wk | Clinician-Administered PTSD Scale (CAPS), PTSD Checklist-Military (PCL-M), Treatment Outcome PSTD Scale (TOP-8) | PCL-M scores significantly lower post-treatment (38.71 +− 13.91) and one wk post-treatment (33.29 +−16.62) than baseline (33.29 +−16.62). TOP-8 scores significantly lower post-treatment (11.57 +−6.21) and one wk post-treatment (11.14 +−8.84) than baseline (24 +−5.23). Decrease in depression and anxiety symptom severity. | No adverse events aside from brief scalp irritation
Koski, 2015^93^; N=12 | TBI | rTMS; NR | PCS Scale | PCS scores declined on average by 14.6 points (p=0.009) | Two participants withdrew because of worsening symptoms. Side effects included increased headache, greater sleep disturbance.
Leung, 2016^72^; N=6 | TBI | rTMS; NR | Numerical rating scale (NRS) for pain relief | Average pre and post-rTMS NRS scores were 5.50 +− 1.38 and 2.67 +−1.75, respectively. Average headache exacerbation frequency (episodes per wk) reduced by 78.97% (+− 19.88). | None reported

Abbreviations: Verbal rating scale (VRS), Duration of pain relief (DPR), Numeric rating scale (NRS), Neuropathic pain symptom inventory (NPSI), Pain relief score (PRS), Visual analogue scale (VAS), Visual numerical scale (VNS), Clinician-Administered PTSD Scale (CAPS), PTSD Checklist-Military (PCL-M), Treatment Outcome PSTD Scale (TOP-8), PTSD Checklist (PCL), Quick Inventory of Depressive Symptomatology (QIDS), Emotional Regulation Scale (DERS), Impact of Event Scale (IES), Difficulties in Emotional Regulation Scale (DERS), Self-Report (IDS-SR), Major depression disorder (MDD)

### APPENDIX G QUALITY ASSESSMENT TABLES

#### QUALITY ASSESSMENT OF RCTS

Author, Year | Risk of bias from randomization process | Risk of bias from deviation from intended interventions (assignment) | Risk of bias from deviation from intended interventions (adherence) | Risk of bias from missing outcome data | Risk of bias in measurement of the outcome | Risk of bias in selection of the reported results | Overall bias (High, Low, Unclear)
Altas, 2019^51^ | Unclear; Computer generated blocked random allocation sequence. Statistically significant differences between groups at baseline in visual analog scale, fatigue severity scale, physical functioning, bodily pain. Unclear allocation concealment. | Low; Participants and researchers blind to allocation. Unclear blinding of rTMS provider. | Low; Participants and researchers unaware of assignment. All participants completed treatment. | Low; No reported missing data. | Unclear; Outcome assessor blinded but outcome self-report. | Unclear; Protocol not readily accessible. | Unclear
Cheng, 2019^53^ | Low; Computerized random number generator with block randomization method. Independent research assistant performed randomization. Researchers and patients blind to block size. Baseline characteristics similar. | Low; Participants and outcome assessors blind to assignments. Unclear if blinding of rTMS provider | Low; Participants blind to assignments. All but 1 participant completed treatment. | Low; No reported missing data. One participant withdrew from study. | Unclear; Outcome assessor blinded but outcome self-report. | Low; All outcomes listed in protocol were reported. | Low
Fitzgibbon, 2018^54^ | Low; Computer number sequence by independent researcher. Blinded allocation. Baseline characteristics similar. | Low; Participants and outcome assessors blind to assignments. Unclear if blinding of rTMS provider | Low; Participants blind to assignments. >95% of participants received allocated intervention. | Low; >85% completed follow-up. Intent-to-treat analysis. | Unclear; Outcome assessor blinded but outcome self-report. | Low; All outcomes listed in protocol were reported. | Low
Guinot, 2019^55^ | Unclear; Computer-generated randomization. Researchers and physiotherapists blind to allocation. Baseline characteristics similar, except control group had 21% men while the intervention had 0%. Unclear allocation concealment. | Low; Participants and outcome assessors blind to assignments. rTMS provider not blinded. | Unclear; Participants blind to assignments. ~14% withdrew during treatment. | Low; ~85% completed follow-up. Intent-to-treat analysis. | Unclear; Outcome assessor blinded but outcome self-report. | Low; Didn’t use Covi Anxiety Scale to measure anxiety. Other outcomes measures consistent with trial registration. | Unclear
Bilir, 2020^52^ | Low; Computer generated block randomization. Independent researcher performed allocation. Participants blinded to allocation. Baseline characteristics similar. | Low; Participants and outcome assessors blind to assignments. rTMS provider not blinded, but independent from others in the study. | Low; Participants blind to assignments. All participants received allocated intervention. | Low; No missing data reported, no participants withdrew/excluded. | Unclear; Outcome assessor blinded but outcome self-report. | Low; All outcomes listed in protocol were reported. | Low
Mattoo, 2019^56^ | Low; Computer-generated random numbers in blocks of 10. Participants blinded to assignments. Different investigators performed randomization, evaluation, and assignment. Baseline characteristics similar. | Low; Participants and assessors blind to assignments. Unclear blinding of rTMS providers. | Low; Participants blind to assignments. No flow diagram but appears all participants completed intervention. | Low; No missing data reported. No participants withdrew/ excluded. | Unclear; Outcome assessor blinded but outcome self-report. | Low; All outcomes listed in protocol were reported. | Low
Sahu, 2019^57^ | Unclear; Alternate allocation. Says “double-blind”, but limited information on blinding methods. Baseline characteristics similar. | Low; Participants and assessors likely blinded. Unclear blinding of rTMS providers. | High; 21% had to be dropped out of the study, unclear timing of drop-out. | High; 21% had to be dropped out of the study, no information on handling of missing data. | Unclear; Outcome assessor blinded but outcome self-report. | Unclear; Protocol not readily accessible. | Unclear
Ahmed 2020^1^ | Low; Computer-generated randomization card by blinded research assistant. Allocation blinded. Baseline characteristics similar. | Unclear; Unclear if participants or researchers blind to assignment. | Low; No flow diagram, but appears that all participants completed the intervention. | Low; No missing data reported. No participants withdrew/excluded. | Unclear; Unclear if outcome assessors blind to assignments. | Unclear; Protocol not readily accessible. | Unclear
Andre-Obadia 2018^43^ | Unclear; No information about randomization process or allocation concealment. No comparison of baseline characteristics. | Unclear; Only participants blinded. Outcome assessors and rTMS providers not blinded. | Unclear; Participants blinded. No information on adherence to interventions. | Unclear; No information on withdrawal or missing data. | High; Outcome assessor unblinded and outcome self-report | Unclear; Protocol not readily accessible. | High
Galhardoni 2019^44^ | Low; Randomization performed with electronic software (randomizer.com). Allocation concealed. Baseline characteristics similar. | Low; Participants and researchers blind to assignments. rTMS providers not blinded. | Low; ~2% didn’t complete intervention | Low; 3 participants withdrew. Missing data imputation performed using k-nearest neighbor algorithm (n=5). | Unclear; Outcome assessor blinded but outcome self-report. | Low; All outcomes listed in protocol were reported. | Low
Hosomi, 2020^45^ | Low; Computer randomization using minimization method. Allocated concealed using allocation function of EDC system. Participants blind to assignment. Baseline characteristics similar. | Low; Participants and assessors blind to assignments. rTMS providers unblinded. | Low; 97% completed interventions. | Low; 95% completed follow-up. Missing data handled without imputation. Intent-to-treat and per-protocol analysis. | Unclear; Outcome assessor blinded but outcome self-report. | Low; All outcomes listed in protocol were reported. | Low
Kim, 2020^46^ | Low; A randomization sequence of blocks was generated by a computer and concealed using opaque envelopes. No baseline differences between groups. | Low; Patients and assessors likely blinded. Unclear blinding of providers. | Low; All participants received intervention/sham condition as allocated (1 withdrew due to unrelated injury). | Low; No participants lost to follow-up. >95% completed follow-up (1 withdrew due to unrelated injury). | Unclear; Outcome assessor blinded but outcome self-report. | Unclear; Protocol not readily accessible. | Low
Quesada, 2020^47^ | Unclear; Randomization and data collection were performed using REDCap electronic data capture tools. Allocation concealment not described (but appeared to be carried out within REDCap). | Low; Patients, assessors, and providers blinded to intervention condition. Patients assessed for awareness of intervention receipt (guessing protocol). | Low; All participants received intervention/sham condition as allocated (14% of each group lost/withdrew after treatment). | Unclear; Relatively low missing data (14% of each group lost to follow-up/ withdrew) but single imputation (last/baseline observation carried forward) used to facilitate ITT analysis. | Unclear; Outcome assessor blinded but outcome self-report. | Low; All outcomes listed in protocol were reported. | Unclear
Shimizu, 2017^94^ | Unclear; Randomization mechanism not described. Independent data center determined the order of stimulation. Allocation concealed using unlabeled magnetic card that changed mode of operation of TMS device. Baseline differences not examined. | Unclear; Patients were blinded to condition, but may have been able to distinguish between different types of TMS because of different coils (received more than one type because crossover trial). Patients assessed for awareness of intervention receipt (guessing protocol). Unclear blinding of providers. | Low; All participants received intervention/sham condition as allocated. | Low; No missing outcome data. | Unclear; Outcome assessor blinded but outcome self-report. | Low; All outcomes listed in protocol were reported. | Unclear
Sun, 2019^48^ | Unclear; Computer generated randomization method. No baseline differences between groups. Unclear allocation concealment | Low; Participants and assessors blinded to treatment group. Unclear if rTMS delivered by independent researchers. | Unclear; Participants blinded. ~80% completed protocol | Unclear; 3 participants in rTMS group and 1 from sham group withdrew during the trial. No description of handling of missing data. | Unclear; Outcome assessor blinded but outcome self-report. | Unclear; Protocol not readily accessible. | Unclear
Ahmadiza deh, 2018^58^ | Unclear; Randomization conducted by statistician (unclear mechanism). Allocation concealment not described. No baseline differences between groups on demographic or clinical variables. | Low; Patients and assessors were blinded to condition. Providers (rTMS technician) unblinded to condition. | Unclear; 25% withdrew or were lost to follow-up. | High; Moderate loss to follow up and use of last observation carried forward. | Unclear; Outcome assessor blinded but some outcomes self-reported. | Unclear; Protocol not readily accessible. | Unclear
Fryml, 2019^59^ | Unclear; Randomization mechanism not described. Allocation concealed using unlabeled magnetic card that changed mode of operation of TMS device. Higher CAPS score and lower depression score in experimental group (no statistical testing). | Low; Patients and assessors were blinded to condition. Unclear blinding of providers. | Low; All participants received intervention/sham as allocated. | High; Reported outcomes appear to have complete data, but several outcomes not reported because of incomplete data. No attempt to handle missing data. | Unclear; Outcome assessor blinded but some outcomes self-reported. | High; Several outcomes not reported due to incomplete data. | High
Isserles, 2013^60^ | Unclear; Randomization and allocation concealment procedures not described. No baseline differences between groups. | Low; Patients and assessors were blinded to condition. Providers appear to have been unblinded. | Low; ~10% of patients withdrew from each group, but all interventions delivered as allocated. Results presented for all patients (ITT), those reaching treatment criterion, and completers. | Unclear; Results provided for ITT (all patients regardless of assessments completed) but unclear how missing data for non-completers were handled. | Unclear; Outcome assessor blinded but outcome self-report. | Low; All outcomes listed in protocol were reported. | Unclear
Kozel, 2018^61^ | Low; Randomization was generated using computer randomization procedure. Assignments recorded on cards and placed in sealed envelopes that were sequentially numbered by an investigator not involved with the participants. Baseline differences between groups evaluated for completers and noncompleters. | Low; Patients and assessors were blinded to condition. TMS providers unblinded but “were isolated from other study staff members and only had minimal interaction with participants during TMS treatment”. | Unclear; Substantial withdrawal after allocation. Significantly different baseline characteristics and outcomes for those who completed therapy versus those who withdrew, but differences were not specific to group. | Unclear; ITT analyses conducted with missing data handled via maximum likelihood. High level of missing data. | Unclear; Outcome assessor blinded but outcome self-report. | Low; All outcomes listed in protocol were reported. | Unclear
Kozel, 2019^62^ | Low; Randomization was generated using a computer randomization. Assignments placed in envelopes prior to trial. No baseline differences between groups. | High; Patients and providers unblinded to condition. Assessors blinded. | Unclear; ~25% lost to follow up or withdrew, but all interventions delivered as allocated. | Unclear; Patients who withdrew after allocation were not analyzed (6); patients lost to follow up (2) were retained. | Unclear; Outcome assessor blinded but outcome self-report. | Low; All outcomes listed in protocol were reported. | Unclear
Leong, 2020^63^ | Low; Participants were randomized by random sequence generation 2:2:1:1 with allocation concealment by the envelope method. No baseline differences between groups. | Low; Patients and assessors blinded but providers unblinded. | Unclear; Minimal but significantly different withdrawal/attrition between groups. | Unclear; Minimal loss to follow-up/ withdrawal, but 3-month outcomes not reported due to differential attrition. | Unclear; Outcome assessor blinded but outcome self-report. | Unclear; Protocol not readily accessible. Three-month outcomes not reported due to differential attrition. | Unclear
Nam, 2013^64^ | Unclear; Random sequence and allocation concealment method not described. No baseline differences between groups. | Low; Patient blinded but provider unblinded (though provider was “blind to all subject information and blocked from communicating about subjects with raters. Prior to the study, the experimenter was trained to maintain a consistent and neutral attitude toward each practice to minimize biases.”) | Low; ~90% received treatment as allocated (2 withdrew from treatment group). | Low; All assessments complete with the exception of 2 withdrawals after allocation. | Unclear; Outcome assessor blinded but outcome self-report. | Unclear; Protocol not readily accessible. | Low
Philip, 2019^66^ | Unclear; Random sequence and allocation concealment method not described. Baseline differences not evaluated. | Unclear; Patients blinded to condition. Patients assessed for awareness of intervention receipt (guessing protocol). Unclear blinding of providers and assessors. | Low; Appears that all patients received treatment as allocated. | Low; No missing outcome data. | Unclear; Unclear assessor blinding and outcome self-report. | Low; All outcomes listed in protocol were reported. | Unclear
Philip, 2019 (iTBS)^67^ | Unclear; Randomization performed by uninvolved study member (mechanism not described). Staff uninvolved in treatment delivery selected coil to conceal randomization. No baseline differences between groups. | Low; Patients and assessors blinded to condition. Patients assessed for awareness of intervention receipt (guessing protocol). Unclear blinding of providers. | Low; <10% withdrew; CONSORT diagram suggests that all patients received treatment as allocated. | Low; Missing outcome data were addressed using multiple imputation. | Unclear; Blinded assessors but outcome self-report (neuroimaging outcomes in convenience subgroup). | Low; All outcomes listed in protocol were reported. | Low
Watts, 2012^68^ | Unclear; Subjects randomly assigned, but no details on methods of randomization. Unclear allocation concealment. Appears that rTMS group may have more comorbidities, but no statistical test performed. | Low; Participants and outcome assessors masked to intervention assignment. | Unclear; No data on intervention adherence. | Unclear; No information on handling of missing data. | Unclear; Outcome assessor blinded but outcome self-report. | Unclear; Protocol not readily accessible. | Unclear
Choi 2018^69^ | Unclear; Computer generated random number sequence. No baseline differences between groups. Unclear method of allocation concealment. | Low; Participants and outcome assessors masked to intervention assignment. | Low; Study states that all patients completed rTMS sessions. | Low; No missing outcome data. | Unclear; Outcome assessor blinded but outcome self-report. | Unclear; Protocol not readily accessible. | Unclear
Hoy, 2019^70^ | Unclear; Computer generated random number sequence. No baseline differences between groups, except use of antidepressant medication. Unclear method of allocation concealment. | Low; Participants and outcome assessors masked to intervention assignment. Neither able to guess treatment group. | Unclear; 14% of patients withdrew, no other information on adherence to interventions. | Unclear; 14% of patients withdrew, no information on handling of missing data. | Unclear; Outcome assessor blinded but outcome self-report. | Low; All outcomes listed in protocol were reported. | Unclear
Lee, 2018^71^ | Unclear; Unclear randomization method. Allocation concealed by sealed envelopes. No baseline differences between groups, except weight. | Unclear; Participants blinded but unclear if outcome assessors masked to intervention assignment. | Low; Flow diagram states that all subjects completed the trial. | Low; No missing outcome data. | Unclear; Outcome assessment appropriate but unclear if outcome assessors were blinded to intervention assignment and outcome self-report. | Unclear; Protocol not readily accessible. | Unclear
Leung, 2016^72^ | Unclear; Computer generated random number sequence. No baseline differences between groups. Unclear method of allocation concealment. | Unclear; Participants blinded but unclear if outcome assessors masked to intervention assignment (participants self-rated headache outcomes, but other outcomes unclear). | Unclear; >80% received allocated intervention. | High; Missing data on 5 (17%) subjects excluded from analysis. Complete case analysis carried out with relatively substantial amount of missing data. | Unclear; Outcome assessment appropriate but unclear if outcome assessors were blinded to intervention assignment (participants self-rated headache outcomes, but other outcomes unclear). | Unclear; Protocol not readily accessible. | Unclear
Leung, 2018^73^ | Unclear; Computer generated random number sequence. No baseline differences between groups. Unclear method of allocation concealment. | Unclear; Participants blinded but unclear if outcome assessors masked to intervention assignment (participants self-rated headache outcomes, but other outcomes unclear). | Low; >90% received allocated intervention. | Unclear; Missing data on 3 (9.4%) subjects excluded from analysis. Complete case analysis carried out, but relatively small amount of missing data. | Unclear; Outcome assessment appropriate but unclear if outcome assessors were blinded to intervention assignment (participants self-rated headache outcomes, but other outcomes unclear). | Unclear; Protocol not readily accessible. | Unclear
Neville, 2019^75^ | Low; Computer generated random number sequence. No significant differences between groups at baseline. Allocation concealed using opaque envelope | Low; Participants and outcome assessors masked to intervention assignment. Unclear blinding of rTMS providers. | Unclear; >80% received allocated intervention. | High; 6 participants (16.6%) did not complete study and were excluded from analysis. Complete case analysis carried out with relatively substantial amount of missing data. | Low; Outcome assessment appropriate. Outcome assessors blinded to intervention assignment. | Low; All outcomes listed in protocol were reported. | Unclear
Rao, 2019^76^ | Unclear; Computer generated random number sequence. No baseline differences between groups, except for higher fatigue in control group. Unclear method of allocation concealment. | Unclear; Participants blinded but unclear if outcome assessors masked to intervention assignment. | Unclear; >80% received allocated intervention. | Low; Missing values imputed, but unclear use on imputations. Missing data only in treatment group. | Unclear; Outcome assessment appropriate but unclear if outcome assessors were blinded to intervention assignment. | Unclear; Protocol not readily accessible. | Unclear
Siddiqi, 2019^77^ | Unclear; Computer generated random number sequence. No baseline differences between groups. Unclear method of allocation concealment. | Low; Participants, outcome assessors, and other study researchers were blinded, except those administering TMS. | Unclear; 2 subjects (15%) did not complete the treatment (1 in each group). | Unclear; No information on handling of missing data. | Unclear; Outcome assessor blinded but outcome self-report. | Unclear; Secondary outcome listed in protocol (tinnitus) not reported | Unclear
Stilling, 2020^78^ | Low; Computer generated random number sequence. No significant differences between groups at baseline (sham group older with less preventive medications). Allocation concealed using opaque envelope | Low; Participants, outcome assessors, and other study researchers were blinded, except those administering TMS. | Low; Flow diagram states that all subjects completed the trial. | Low; No missing outcome data. | Unclear; Outcome assessor blinded but outcome self-report. | Low; All outcomes listed in protocol were reported. | Low
Liu, 2020^79^ | Low; Computer generated random number sequence. No baseline differences between groups. Unclear allocation concealment. | Low; Participants blinded to treatment group. rTMS delivered by independent researchers | Unclear; >80% received allocated intervention. | Unclear; >80% followed-up at 90 days. No description of handling of missing data. | Unclear; Outcome assessors different from those delivering intervention, unclear blinding and outcomes self-report. | Low; All outcomes listed in protocol were reported. | Unclear
Shen, 2016^80^ | Unclear; No information about randomization process. | Unclear; No information about blinding or deviations from protocol. | Unclear; No information about blinding of participants or researchers. No information about intervention adherence. | Unclear; No information on loss to follow-up or handling of missing data. | Unclear; Unknown if outcome assessors were different from those delivering intervention, unclear blinding, and outcomes self-report. | Low; All outcomes listed in protocol were reported. | Unclear

Petrosino 2020 not rated, same study as Philip 2019

#### QUALITY ASSESSMENT OF COHORT STUDIES

Author Year | Selection bias | Bias in classification of interventions | Bias due to departures from intended interventions | Bias due to measurement of outcomes | Bias due to confounding | Bias due to missing data | Bias in the selection of reported results | Overall bias (High, Low, Unclear)
Abd Elghany 2019^50^ | Unclear; Minimal info on how participants were selected. Study indicates groups were matched in age, sex, and disease duration, but no data presented. No adjustment for other potential confounders. | Unclear; No info on how participants were placed into intervention groups. | Unclear; No info on intervention adherence or potential co-interventions | Unclear; Subjective outcome measures may be influenced by knowledge of intervention. Unclear masking of outcome assessors. | High; Potential for confounding based on disease severity, unclear balance of disease severity across groups. Very limited controlling for confounding. | Unclear; No description of handling of missing data. | Unclear; Protocol not readily accessible. | High
Manko, 2013^74^ | High; Unclear how patients were selected into study. No information on baseline characteristics of patients. No adjustment for potential confounders. | Unclear; Patients divided numerically into intervention groups. No other information on how participants were selected into groups. | Unclear; No info on intervention adherence or potential co-interventions | Unclear; Subjective outcome measures may be influenced by knowledge of intervention. Unclear masking of outcome assessors. | High; Potential for confounding based on patient and disease characteristics and unclear balance of characteristics across groups. No controlling for confounding. | Unclear; No description of handling of missing data. | Unclear; Protocol not readily accessible. | High
Gaertner, 2018^49^ | Unclear; Minimal info on how participants were selected. Unclear if groups were balanced at baseline. | Unclear; Patients self-selected into intervention groups. Unclear if patient or disease characteristics related to outcome may influence selection. | High; Differential attrition between groups. 19% did not complete full protocol. | Unclear; Subjective outcome measures may be influenced by knowledge of intervention. Unclear masking of outcome assessors. | High; Potential for confounding based on patient and disease characteristics and unclear balance of characteristics across groups. No controlling for confounding. | Unclear; No description of handling of missing data. | Low; All outcomes listed in protocol were reported | High

### APPENDIX H STRENGTH OF EVIDENCE

Author, Year; N | Primary Outcome(s) | Findings | Quality | Strength of Evidence
Complex Regional Pain Syndrome
Gaetner, 2018^49^; 21 | Pain: VAS, NRS | Both groups demonstrated significant pain reduction after 1-wk posttreatment; but no differences between groups. | High | Very Low SOE; It is unclear whether TMS may improve pain compared to sham. Very limited confidence due to 1 small cohort with high RoB.
Fibromyalgia
Abd Elghany, 2019^*^,^50^; 120 | Pain: VAS, SF-MPQ, NRS | Significant decrease in mean VAS score with rTMS immediately after treatment and at 1 month and with injection therapy immediately after treatment and at 1 month. Injection therapy had lower pain scores at baseline and 1 month compared to rTMS. | High | Low SOE; TMS may be no better than sham in pain improvement. Limited confidence due 6 small studies with low to high RoB.
Atlas, 2019^51^; 30 | Pain: VAS, SF-MPQ, NRS | Significant improvements from baseline in VAS score in M1, DLPFC, and sham groups. Decrease in VAS significantly greater in Group M1 vs sham, but not DLPFC vs sham, or M1 vs DLPFC. | Unclear | Low SOE; TMS may be no better than sham in pain improvement. Limited confidence due 6 small studies with low to high RoB.
Bilir, 2020^52^; 26 | Pain: VAS, SF-MPQ, NRS | There was no significant difference in VAS-pain over time or between groups. | Low | Low SOE; TMS may be no better than sham in pain improvement. Limited confidence due 6 small studies with low to high RoB.
Cheng, 2019^53^; 20 | Pain: VAS, SF-MPQ, NRS | Decrease in pain score (VAS) with rTMS, but not with sham. No significant difference in pain between groups at wk 1 or wk 2. | Low | Low SOE; TMS may be no better than sham in pain improvement. Limited confidence due 6 small studies with low to high RoB.
Fitzgibbon, 2018^54^; 26 | Pain: VAS, SF-MPQ, NRS | Pain improved at 1 month vs baseline in both rTMS and sham groups on all pain measures. No significant differences between groups was observed. rTMS group significantly more likely to respond (achieve a minimum 30% improvement in pain intensity ratings) than sham. | Low | Low SOE; TMS may be no better than sham in pain improvement. Limited confidence due 6 small studies with low to high RoB.
Guinot, 2019^55^; 26 | Pain: VAS, SF-MPQ, NRS | Pain improved after therapy (wk 14) and at 6-month follow-up for both rTMS and sham groups. No differences in pain reduction between groups. | Low | Low SOE; TMS may be no better than sham in pain improvement. Limited confidence due 6 small studies with low to high RoB.
Headache
Mattoo, 2019^56^; 30 | Pain: NRS, Headache symptoms | NRS score decreased significantly in the rTMS group compared to placebo. | Low | Moderate SOE; TMS probably improves headache pain and symptoms compared to sham. Limited confidence due to small studies with low to unclear RoB.
Sahu, 2019^57^; 41 | Pain: NRS, Headache symptoms | There was a greater decrease in frequency, duration, and severity of migraine in the active group compared to the sham group over the study period. | Unclear | Moderate SOE; TMS probably improves headache pain and symptoms compared to sham. Limited confidence due to small studies with low to unclear RoB.
Neuropathic
Ahmed, 2020^1^; 30 | Pain: VAS, NRS | Decrease in pain severity at 1 wk from baseline in both groups, but no differences between groups. | Unclear | Low SOE; TMS may improve pain compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Andre-Obadia, 2018^43^; 35 | Pain: VAS, NRS | rTMS targeted over the hand motor cortex had greater pain relief than rTMS targeted over facial cortex face rTMS and sham. | High | Low SOE; TMS may improve pain compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Galhardoni, 2019^44^; 100 | Pain: VAS, NRS | NRS score was not significantly different between groups at any point during the study. | Low | Low SOE; TMS may improve pain compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Hosomi, 2020^45^; 144 | Pain: VAS, NRS | Pain improvement not significantly different between the rTMS and sham groups during the daily sessions. No difference in number of responders (> 10mm decrease VAS) between rTMS and sham. | Low | Low SOE; TMS may improve pain compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Kim, 2020^46^; 30 | Pain: VAS, NRS | S-LANSS decreased more in iTBS vs sham groups. NRS decreased more in iTBS vs sham. | Low | Low SOE; TMS may improve pain compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Quesada, 2020^47^; 42 | Pain: VAS, NRS | Percent of pain relief (%R) was greater after rTMS phase compared to sham phase. 54% (rTMS) vs 21% (sham) achieved >30% pain relief and 35% (rTMS) vs 12% (sham) achieved >50% pain relief. Significant decrease in VAS after rTMS phase but not sham phase. | Low | Low SOE; TMS may improve pain compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Shimizu, 2017^94^; 18 | Pain: VAS, NRS | VAS improved significantly immediately after deep rTMS and 1-hour after deep rTMS compared with sham. No significant pain improvement with rTMS immediately after or 1-hour compared with sham. No significant long-term effects on VAS scores for any type of stimulation. | Unclear | Low SOE; TMS may improve pain compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Sun, 2019^48^; 21 | Pain: VAS, NRS | Pain intensity decreased from baseline to 6 wks in rTMS group and sham group. Pain intensity decreased more in rTMS group compared to sham and the difference became significant at wk 2. | Unclear | Low SOE; TMS may improve pain compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
PTSD
Ahmadizadeh, 2018^58^; 65 | PTSD symptoms: PCL, CAPS | Greater proportion of responders (≥ 2 std from mean PCL) in rTMS groups compared to sham and no difference between bilateral and unilateral groups. Significant mean improvement in PCL in unilateral and bilateral rTMS vs sham after all sessions | Unclear | Low SOE; TMS may improve PTSD symptoms compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Fryml, 2019^59^; 8 | PTSD symptoms: PCL, CAPS | No difference in reduction in CAPS scores with rTMS compared with sham at session 5. | High | Low SOE; TMS may improve PTSD symptoms compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Isserles, 2013^60^; 30 | PTSD symptoms: PCL, CAPS | CAPS score improved significantly in rTMS + trauma imagery group, but not in rTMS + positive imagery group, or sham group. | Unclear | Low SOE; TMS may improve PTSD symptoms compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Kozel, 2018^61^; 103 | PTSD symptoms: PCL, CAPS | Total CAPS score had a greater decrease from baseline in rTMS compared to sham group. | Unclear | Low SOE; TMS may improve PTSD symptoms compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Kozel, 2019^62^; 35 | PTSD symptoms: PCL, CAPS | No difference in CAPS response or remission after 30 sessions. Improved CAPS score with 1 Hz and 10 Hz rTMS after 30 sessions. No significant difference between groups. | Unclear | Low SOE; TMS may improve PTSD symptoms compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Leong, 2020^63^; 31 | PTSD symptoms: PCL, CAPS | PTSD symptoms improved at the end of treatment with 1 Hz rTMS compared to sham, but not with 10 Hz rTMS compared to sham. There was a significant time x treatment effect over the 3-month follow-up. | Unclear | Low SOE; TMS may improve PTSD symptoms compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Nam, 2013^64^; 18 | PTSD symptoms: PCL, CAPS | PTSD symptoms improved for all groups but no significant effect of treatment group. Significant effect of time x treatment. | Low | Low SOE; TMS may improve PTSD symptoms compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Philip, 2019^67^ (iTBS); 50 | PTSD symptoms: PCL, CAPS | No difference in PTSD symptoms (CAPS) between groups after treatment (2 wks). At 1-month (after unblinded phase) iTBS had greater PTSD symptom improvement compared to sham. More patients responded (> 12-point CAPS reductions) with iTBS compared to sham. | Low | Low SOE; TMS may improve PTSD symptoms compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Philip, 2019^66^; 23 | PTSD symptoms: PCL, CAPS | All participants demonstrated significant reductions in PTSD and MDD symptoms. No significant differences between groups. | Unclear | Low SOE; TMS may improve PTSD symptoms compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Watts, 2012^68^; 20 | PTSD symptoms: PCL, CAPS | rTMS group had significant reduction in PTSD symptoms compared with sham after treatment (2 wks). CAPS scores remained significantly improved from baseline at 2 months post-treatment, but 6/10 participants had s 10-point worsening in PTSD symptoms from post-treatment to 2 months. | Unclear | Low SOE; TMS may improve PTSD symptoms compared to sham. Limited confidence due to inconsistent findings and low to high RoB.
Petrosino, 2020^65^; 46 | Clinical relapse^*^ | Overall, 47.8% of patients had clinical relapse. Fewer patients in active iTBS group had relapse compared to sham (OR relapse = 3.5, 95% Cl 1.04 to 11.79). | Low | Low SOE; TMS may improve clinical relapse compared to sham in PTSD patients. Limited confidence due to single study.
TBI
Choi, 2011^69^; 12 | Pain: Numerical rating scale (NRS) | Changes in NRS over time were significantly different between groups. NRS score significantly lower in rTMS group compared to sham group at each follow-up point. | Unclear | Low SOE:; TMS may improve pain compared to sham. Limited confidence due to single, small study with unclear RoB.
Hoy, 2019^70^; 21 | Depressive symptoms: MADRS, HAM-D | Significant improvement in depressive symptoms (MADRS) for both groups, but no differences between groups. | Unclear | Low SOE:; TMS may improve depressive symptoms compared to sham. Limited confidence due to inconsistent findings and unclear RoB.
Lee, 2018^71^; 13 | Depressive symptoms: MADRS, HAM-D | Significant improvements in depressive symptoms after rTMS, but not after sham. | Unclear | Low SOE:; TMS may improve depressive symptoms compared to sham. Limited confidence due to inconsistent findings and unclear RoB.
Rao, 2019^76^; 35 | Depressive symptoms: MADRS, HAM-D | No statistically significant differences between groups in changes in HAM-D scores or on rates of remission or response. HAM-D scores varied widely, favoring rTMS at some time points and sham at others. | Unclear | Low SOE:; TMS may improve depressive symptoms compared to sham. Limited confidence due to inconsistent findings and unclear RoB.
Siddiqi, 2019^77^; 15 | Depressive symptoms: MADRS, HAM-D | Mean MADRS improvement was greater with rTMS than with sham. Hypothesis testing not completed due to study termination. | Unclear | Low SOE:; TMS may improve depressive symptoms compared to sham. Limited confidence due to inconsistent findings and unclear RoB.
Leung, 2016^72^; 24 | Headache symptoms: headache diary | More patients in rTMS group had > 50% headache reduction compared to sham. Composite score of debilitating headache exacerbation significantly reduced in rTMS group at 4 wks while sham did not. | Unclear | Low SOE:; TMS may improve headache symptoms compared to sham. Limited confidence due to inconsistent findings and low to unclear RoB.
Leung, 2018^73^; 29 | Headache symptoms: headache diary | Signification reduction in average daily persistent headache intensity with rTMS but not sham at 1- and 4-wks. Significant reduction in % of patients no longer experiencing persistent headaches with rTMS but not sham at 1- and 4-wks. | Unclear | Low SOE:; TMS may improve headache symptoms compared to sham. Limited confidence due to inconsistent findings and low to unclear RoB.
Stilling, 2020^78^; 20 | Headache symptoms: headache diary | Significant overall time effect for average headache severity but no effect of treatment group at 1-month post-treatment. | Low | Low SOE:; TMS may improve headache symptoms compared to sham. Limited confidence due to inconsistent findings and low to unclear RoB.
Choi, 2018^69^; 12 | Quality of Life: SF-36, Quality of Life Evaluation Scale, Quality of Life after - Brain Injury Questionnaire | SF-36 physical component scores increased more in rTMS group compared to sham group at each time point, but SF-36 mental component scores did not change significantly over time. | Unclear | Low SOE:; Unclear whether TMS improves quality of life. Limited by inconsistent findings and low to high RoB.
Manko, 2013^74^; 40 | Quality of Life: SF-36, Quality of Life Evaluation Scale, Quality of Life after - Brain Injury Questionnaire | Mental and physical comfort significantly improved with rTMS (p<0.001) but not in control group (p=.0797). | High | Low SOE:; Unclear whether TMS improves quality of life. Limited by inconsistent findings and low to high RoB.
Stilling, 2020^78^; 20 | Quality of Life: SF-36, Quality of Life Evaluation Scale, Quality of Life after - Brain Injury Questionnaire | There was a significant time effect for quality of life, but no differences between groups. | Low | Low SOE:; Unclear whether TMS improves quality of life. Limited by inconsistent findings and low to high RoB.
Hoy, 2019^70^; 21 | Function: Trail Making Test, Conner’s Continuous Performance Test | Improvement in Trail Making Test (B) with rTMS, but no difference between groups. | Unclear | Low SOE:; Unclear if rTMS improves function compared to sham. Confidence limited by inconsistent findings and unclear RoB.
Leung, 2016^72^; 24 | Function: Trail Making Test, Conner’s Continuous Performance Test | No difference in Conner’s Continuous Performance (CPT) at wks 1 or 4 between groups. Significant interaction of visit and treatment at 1 wk, with an increase in CPT score with rTMS, but decrease in CPT score with sham | Unclear | Low SOE:; Unclear if rTMS improves function compared to sham. Confidence limited by inconsistent findings and unclear RoB.
Leung, 2018^73^; 29 | Function: Trail Making Test, Conner’s Continuous Performance Test | No overall interaction between group and time on Conner’s Continuous Performance (CPT). | Unclear | Low SOE:; Unclear if rTMS improves function compared to sham. Confidence limited by inconsistent findings and unclear RoB.
Neville, 2019^75^; 36 | Function: Trail Making Test, Conner’s Continuous Performance Test | No differences in executive function between groups or in time x group interactions. rTMS group improved significantly at 90-days compared to baseline. | Unclear | Low SOE:; Unclear if rTMS improves function compared to sham. Confidence limited by inconsistent findings and unclear RoB.
Rao, 2019^76^; 34 | Function: Trail Making Test, Conner’s Continuous Performance Test | Effects on neuropsychological functioning varied and favored rTMS for some measures and sham for others. | Unclear | Low SOE:; Unclear if rTMS improves function compared to sham. Confidence limited by inconsistent findings and unclear RoB.
Opioids
Liu, 2020^79^; 118 | Craving score: subjective 0-100 scale | Craving scores decreased more in first 30 days in both 1 Hz and 10 Hz groups, compared to control. All groups had significantly reduced craving score at 30, 60, and 90 days compared to baseline. | Unclear | Moderate SOE:; TMS may improve craving scores compared to sham. Limited by unclear RoB.
Shen, 2016^80^; 20 | Craving score: subjective 0-100 scale | Significant reduction in craving score after rTMS but not after sham rTMS. | Unclear | Moderate SOE:; TMS may improve craving scores compared to sham. Limited by unclear RoB.

* defined as suicide (attempt or otherwise), inpatient psychiatric hospitalization, or need for rTMS retreatment) Abbreviations: iTBS=intermittent theta-burst stimulation; rTMS=repetitive transcranial magnetic stimulation; VAS=visual analog scale; NRS=numerical rating scale; PCL=PTSD symptom checklist; SF-MPQ=Short-Form McGill Pain Questionnaire; MADRS=Montgomery-Asberg Depression Rating Scale; HAM-D=Hamilton Depression Rating Scale; CAPS=Clinician administered PTSD scale; RoB=Risk of bias; S-LANSS=Leeds assessment of neuropathic symptoms and signs; SF-36=short form 36

### PEER REVIEW COMMENTS TABLE

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | None
2 | 2 | Yes | None
Is there any indication of bias in our synthesis of the evidence?
3 | 1 | No | None
4 | 2 | No | None
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
5 | 1 | No | None
6 | 2 | Yes - This depends on the scope of TBI being discussed. Please see below. | We have clarified the scope of TBI. We did not limit to any severity of TBI but have specified the TBI severity in the included studies.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
7 | 1 | I think it would be helpful to provide more detail for each indication what type of TMS has been researched as a treatment for the indication. For instance, under each indication there is a call-out box with the number of studies, level of SOE, number and mean of of participants, and summary of findings. It might be helpful to include in these boxes what type of TMS were used in the studies for each of the indications. This would make it easier for the audience to see for which conditions different types of TMS have been explored. | We have specified in summary statements and in the individual descriptions, which studies are rTMS and which studies are other forms of TMS. We have clarified that most studies are in rTMS throughout.
8 | 1 | I think it would also be helpful in the Summary and Discussion section to include more context for the results, namely that since rTMS was the more commonly utilized protocol of TMS, the results should be understood in the appropriate context. In this section, the authors state “TMS therapy may be effective for treating chronic pain, PTSD, TBI, and opiate addiction” but there is very little evidence to support this conclusion in the context of iTMS, sTMS, and MERT compared to rTMS or deep TMS. Another way to clarify the context might be to include another figure similar to figure 2 (pg 9 line 13) to show the breakdown of the different types of TMS included in the review, perhaps even broken down to show which were studied and in how many papers for each condition (which would also address my previous point). For each indication, broad statements that “TMS may be effective for x” are used but I think the context of WHICH TMS may be effective is important since some varieties have been much more thoroughly studied than others. | We have clarified throughout the report that most of the evidence was for rTMS. We have specified in summary statements and in the individual descriptions, which studies are rTMS and which studies are other forms of TMS. We have updated Figure 2 to reflect the number of studies in rTMS and other TMS therapies.
9 | 2 | The review was very well-written and I have a few suggestions for additional clarity for other readers. Please note that page numbers below refer to the PDF page number and not the page number of the document. | None.
10 | 2 | Page 6 - line 24: It would be more accurate to mention here (as you do later in the document), that TMS stimulation passes through the scalp/skull to stimulate the brain at the cortex. | Changed.
11 | 2 | Page 8 - line 59: While it is true that any stimulation above 100% of resting motor threshold (RMT) increases the risk for seizure. The typical prescription for MDD is to treat at 120% of RMT. Given that this is common practice, it can be confusing for readers and this detail should be included for completeness. | We have added this detail for clarity.
12 | 2 | Page 9 - line 24-25: It is true that the FDA approves the use of a new technology prior before it being used to treat a specific condition. To the best of my knowledge, the FDA approves the initially proposed device. Any additional devices with similar evidence, etc. then must demonstrate the equivalency of their device and it is then “cleared” by the FDA rather than approved. | This wording has been changed for clarity.
13 | 2 | Page 20 - Summary Box: I am not sure if there is a typo in this box or if the age range is just flipped. It is odd to read the lower end of the age range on the right. | This was an error, and the end age range has been fixed.
14 | 2 | General comments:; PAGE 21 - PTSD versus sexual trauma This is a particularly interesting differentiating as it explicitly suggests a couple of differing things: (1) sexual trauma is different from PTSD and/or (2) PTSD resultant from sexual trauma as the criterion A event may manifest itself in a completely different way than other criterion A events. Overall, this implies that the potential underlying neuroanatomical substrates might differ based on type of trauma. The literature does not necessarily support this, but it does suggest that there are other factors which are associated with the incidence of specific types of trauma. All this to say, it is curious as to why sexual trauma is being discussed as a distinct condition. | We agree that there is the potential for these two patient groups to overlap. We included studies of PTSD, regardless of the traumatic event. Patients with sexual trauma may have been included in these studies, but as the traumatic events were not commonly reported, we do not know if, or how many. Since people with sexual trauma may or may not have a diagnosis of PTSD, and may seek treatment without a diagnosis of PTSD, we feel it makes sense to leave sexual trauma in its own category. Moreover, the legislation motivating the request for this review differentiates PTSD from sexual trauma. We have added a couple of sentences to the discussion section to clarify this potential overlap.
15 | 2 | PAGE 22 - TBI symptoms and severity; In order to fully elaborate on this area, it is important to indicate what severity level of TBI you are discussing. Is the evidence limited to mild to moderate TBI, or does it include information regarding severe TBI. Also, does the scope of the question include treating severe TBI resulting in minimally conscious persons? Reading of this gives the impression that only mild TBI is covered. If so, that should be explicitly stated. The description of symptoms treated is also vague and it is unclear what about TBI is being considered. Does the key question want to focus on cognitive sequelae, mood sequelae, those measured and identified on the Neurobehavioral Symptom Inventory (NSI). Additionally, post-concussive symptoms (PCS) could also be considered a separate condition in itself and has a variety of subsequent considerations. In sum, there is a lack of specificity in this area which makes this section less useful than it could be. | We agree that more detail is useful in describing the results of the effect of TMS on TBI. We included any study that examined the use of TMS on TBI symptoms (any post-TBI symptoms and any TBI severity). We have added detail on TBI severity in the specific studies. We have added a sentence to clarify that we were looking at any post-TBI symptoms.

### REFERENCES

1 Ahmed G, Maher EA, Elnassag Baemr Sayed HM, Kabbash SI. Effects of repetitive transcranial magnetic stimulation versus transcutaneous electrical nerve stimulation to decrease diabetic neuropathic pain. International journal of therapy & rehabilitation. 2020;27(2):1–10.
2 André-Obadia N, Peyron R, Mertens P, Mauguière F, Laurent B, Garcia-Larrea L. Transcranial magnetic stimulation for pain control. Double-blind study of different frequencies against placebo, and correlation with motor cortex stimulation efficacy. Clinical neurophysiology. 2006;117(7):1536–1544.16753335
3 André-Obadia N, Mertens P, Gueguen A, Peyron R, Garcia-Larrea L. Pain relief by rTMS: differential effect of current flow but no specific action on pain subtypes. Neurology. 2008;71(11):833–840.18779511
4 André-Obadia N, Magnin M, Garcia-Larrea L. On the importance of placebo timing in rTMS studies for pain relief. Pain. 2011;152(6):1233–1237.21342747
5 Avery DH, Zarkowski P, Krashin D, . Transcranial magnetic stimulation in the treatment of chronic widespread pain: a randomized controlled study. The journal of ECT. 2015;31(1):57–66.24755729
6 Borckardt JJ, Smith AR, Reeves ST, . A pilot study investigating the effects of fast left prefrontal rTMS on chronic neuropathic pain. Pain Medicine. 2009;10(5):840–849.19594842
7 Boyer L, Dousset A, Roussel P, . rTMS in fibromyalgia: a randomized trial evaluating QoL and its brain metabolic substrate. Neurology. 2014;82(14):1231–1238.24670891
8 Carretero B, Martín MJ, Juan A, . Low-frequency transcranial magnetic stimulation in patients with fibromyalgia and major depression. Pain medicine. 2009;10(4):748–753.19460131
9 Dall’Agnol L, Medeiros LF, Torres IL, . Repetitive transcranial magnetic stimulation increases the corticospinal inhibition and the brain-derived neurotrophic factor in chronic myofascial pain syndrome: an explanatory double-blinded, randomized, sham-controlled trial. The Journal of Pain. 2014;15(8):845–855.24865417
10 de Oliveira RAA, de Andrade DC, Mendonça M, . Repetitive transcranial magnetic stimulation of the left premotor/dorsolateral prefrontal cortex does not have analgesic effect on central poststroke pain. The Journal of Pain. 2014;15(12):1271–1281.25267523
11 Defrin R, Grunhaus L, Zamir D, Zeilig G. The Effect of a Series of Repetitive Transcranial Magnetic Stimulations of the Motor Cortex on Central Pain After Spinal Cord Injury. Archives of Physical Medicine and Rehabilitation. 2007;88(12):1574–1580.18047871
12 Fregni F, DaSilva D, Potvin K, . Treatment of chronic visceral pain with brain stimulation. Annals of Neurology. 2005;58(6):971–972.16315281
13 Fregni F, Potvin K, DaSilva D, . Clinical effects and brain metabolic correlates in non-invasive cortical neuromodulation for visceral pain. European Journal of Pain. 2011;15(1):53–60.20822942
14 Hirayama A, Saitoh Y, Kishima H, . Reduction of intractable deafferentation pain by navigation-guided repetitive transcranial magnetic stimulation of the primary motor cortex. Pain. 2006;122(1–2):22–27.16495011
15 Hosomi K, Shimokawa T, Ikoma K, . Daily repetitive transcranial magnetic stimulation of primary motor cortex for neuropathic pain: A randomized, multicenter, double-blind, crossover, sham-controlled trial. PAIN®. 2013;154(7):1065–1072.23623156
16 Irlbacher K, Kuhnert J, Röricht S, Meyer B, Brandt S. Central and peripheral deafferent pain: therapy with repetitive transcranial magnetic stimulation. Der Nervenarzt. 2006;77(10):1196, 1198.16955313
17 Jetté F, Côté I, Meziane HB, Mercier C. Effect of single-session repetitive transcranial magnetic stimulation applied over the hand versus leg motor area on pain after spinal cord injury. Neurorehabil Neural Repair. 2013;27(7):636–643.23579183
18 Kang BS, Shin HI, Bang MS. Effect of repetitive transcranial magnetic stimulation over the hand motor cortical area on central pain after spinal cord injury. Archives of physical medicine and rehabilitation. 2009;90(10):1766–1771.19801069
19 Khedr E, Kotb H, Kamel N, Ahmed M, Sadek R, Rothwell J. Longlasting antalgic effects of daily sessions of repetitive transcranial magnetic stimulation in central and peripheral neuropathic pain. Journal of Neurology, Neurosurgery & Psychiatry. 2005;76(6):833–838.
20 Lee SJ, Kim DY, Chun MH, Kim YG. The Effect of Repetitive Transcranial Magnetic Stimulation on Fibromyalgia: A Randomized Sham-Controlled Trial with 1-Mo Follow-Up. American Journal of Physical Medicine & Rehabilitation. 2012;91(12):1077–1085.23159954
21 Lefaucheur JP, Drouot X, Nguyen JP. Interventional neurophysiology for pain control: duration of pain relief following repetitive transcranial magnetic stimulation of the motor cortex. Neurophysiologie Clinique/Clinical Neurophysiology. 2001;31(4):247–252.11601430
22 Lefaucheur J-P, Drouot X, Keravel Y, Nguyen J-P. Pain relief induced by repetitive transcranial magnetic stimulation of precentral cortex. NeuroReport. 2001;12(13):2963–2965.11588611
23 Lefaucheur J-P, Drouot X, Menard-Lefaucheur I, . Neurogenic pain relief by repetitive transcranial magnetic cortical stimulation depends on the origin and the site of pain. Journal of Neurology, Neurosurgery &amp; Psychiatry. 2004;75(4):612–616.
24 Lefaucheur JP, Drouot X, Ménard-Lefaucheur I, Keravel Y, Nguyen JP. Motor cortex rTMS restores defective intracortical inhibition in chronic neuropathic pain. Neurology. 2006;67(9):1568–1574.17101886
25 Lefaucheur J-P, Drouot X, Ménard-Lefaucheur I, Keravel Y, Nguyen J-P. Motor cortex rTMS in chronic neuropathic pain: pain relief is associated with thermal sensory perception improvement. Journal of Neurology, Neurosurgery &amp; Psychiatry. 2008;79(9):1044–1049.
26 Malavera M, Silva F, García R, Quiros J, Dallos M, Pinzón A. Effects of transcranial magnetic stimulation in the treatment of phantom limb pain in landmine/INS; victims: A randomized clinical trial. Journal of the Neurological Sciences. 2013;333:e534.
27 Medeiros LF, Caumo W, Dussán-Sarria J, . Effect of Deep Intramuscular Stimulation and Transcranial Magnetic Stimulation on Neurophysiological Biomarkers in Chronic Myofascial Pain Syndrome. Pain Medicine. 2016;17(1):122–135.26408420
28 Mhalla A, Baudic S, de Andrade DC, . Long-term maintenance of the analgesic effects of transcranial magnetic stimulation in fibromyalgia. PAIN®. 2011;152(7):1478–1485.21397400
29 Nardone R, Holler Y, Langthaler PB, . rTMS of the prefrontal cortex has analgesic effects on neuropathic pain in subjects with spinal cord injury. Spinal Cord. 2017;55(1):20–25.27241450
30 Nurmikko T, MacIver K, Bresnahan R, Hird E, Nelson A, Sacco P. Motor cortex reorganization and repetitive transcranial magnetic stimulation for pain—a methodological study. Neuromodulation: Technology at the Neural Interface. 2016;19(7):669–678.
31 Onesti E, Gabriele M, Cambieri C, . H-coil repetitive transcranial magnetic stimulation for pain relief in patients with diabetic neuropathy. European Journal of Pain. 2013;17(9):1347–1356.23629867
32 Passard A, Attal N, Benadhira R, . Effects of unilateral repetitive transcranial magnetic stimulation of the motor cortex on chronic widespread pain in fibromyalgia. Brain. 2007;130(10):2661–2670.17872930
33 Picarelli H, Teixeira MJ, de Andrade DC, . Repetitive transcranial magnetic stimulation is efficacious as an add-on to pharmacological therapy in complex regional pain syndrome (CRPS) type I. J Pain. 2010;11(11):1203–1210.20430702
34 Pleger B, Janssen F, Schwenkreis P, Völker B, Maier C, Tegenthoff M. Repetitive transcranial magnetic stimulation of the motor cortex attenuates pain perception in complex regional pain syndrome type I. Neuroscience Letters. 2004;356(2):87–90.14746870
35 Rollnik JD, Wüstefeld S, Däuper J, . Repetitive transcranial magnetic stimulation for the treatment of chronic pain–a pilot study. European neurology. 2002;48(1):6–10.12138303
36 Saitoh Y, Hirayama A, Kishima H, . Reduction of intractable deafferentation pain due to spinal cord or peripheral lesion by high-frequency repetitive transcranial magnetic stimulation of the primary motor cortex. Journal of neurosurgery. 2007;107(3):555–559.17886555
37 Tzabazis A, Aparici CM, Rowbotham MC, Schneider MB, Etkin A, Yeomans DC. Shaped magnetic field pulses by multi-coil repetitive transcranial magnetic stimulation (rTMS) differentially modulate anterior cingulate cortex responses and pain in volunteers and fibromyalgia patients. Mol Pain. 2013;9:33.23819466
38 Short EB, Borckardt JJ, Anderson BS, . Ten sessions of adjunctive left prefrontal rTMS significantly reduces fibromyalgia pain: a randomized, controlled pilot study. Pain. 2011;152(11):2477–2484.21764215
39 Tekin A, Özdil E, Güleken MD, . Efficacy of high frequency [10 Hz] repetitive transcranial magnetic stimulation of the primary motor cortex in patients with fibromyalgia syndrome: a randomized, double blind, sham-controlled trial. Journal of Musculoskeletal Pain. 2014;22(1):20–26.
40 Umezaki Y, Badran BW, DeVries WH, Moss J, Gonzales T, George MS. The efficacy of daily prefrontal repetitive transcranial magnetic stimulation (rTMS) for burning mouth syndrome (BMS): a randomized controlled single-blind study. Brain Stimulation. 2016;9(2):234–242.26597930
41 Yağcı İ, Ağırman M, Öztürk D, Eren B. Is the transcranial magnetic stimulation an adjunctive treatment in fibromyalgia patients? 2014.
42 Yılmaz B, Kesikburun S, Yaşar E, Tan AK. The effect of repetitive transcranial magnetic stimulation on refractory neuropathic pain in spinal cord injury. The Journal of Spinal Cord Medicine. 2014;37(4):397–400.24621025
43 Andre-Obadia N, Magnin M, Simon E, Garcia-Larrea L. Somatotopic effects of rTMS in neuropathic pain? A comparison between stimulation over hand and face motor areas. European Journal of Pain. 2018;22(4):707–715.29194849
44 Galhardoni R, Aparecida da Silva V, Garcia-Larrea L, . Insular and anterior cingulate cortex deep stimulation for central neuropathic pain: Disassembling the percept of pain. Neurology. 2019;92(18):e2165–e2175.30952795
45 Hosomi K, Sugiyama K, Nakamura Y, . A randomized controlled trial of 5 daily sessions and continuous trial of 4 wkly sessions of repetitive transcranial magnetic stimulation for neuropathic pain. Pain. 2020;161(2):351–360.31593002
46 Kim JK, Park HS, Bae JS, Jeong YS, Jung KJ, Lim JY. Effects of multi-session intermittent theta burst stimulation on central neuropathic pain: A randomized controlled trial. Neurorehabilitation. 2020;46(1):127–134.32039876
47 Quesada C, Pommier B, Fauchon C, . New procedure of high-frequency repetitive transcranial magnetic stimulation for central neuropathic pain: a placebo-controlled randomized crossover study. Pain. 2020;161(4):718–728.31764387
48 Sun X, Long H, Zhao C, . Analgesia-enhancing effects of repetitive transcranial magnetic stimulation on neuropathic pain after spinal cord injury:An fNIRS study. Restorative Neurology & Neuroscience. 2019;37(5):497–507.31381538
49 Gaertner M, Kong JT, Scherrer KH, Foote A, Mackey S, Johnson KA. Advancing Transcranial Magnetic Stimulation Methods for Complex Regional Pain Syndrome: An Open-Label Study of Paired Theta Burst and High-Frequency Stimulation. Neuromodulation. 2018;21(4):409–416.29504190
50 Abd Elghany SE, Al Ashkar DS, El-Barbary AM, . Regenerative injection therapy and repetitive transcranial magnetic stimulation in primary fibromyalgia treatment: A comparative study. Journal of Back & Musculoskeletal Rehabilitation. 2019;32(1):55–62.30149440
51 Altas EU, Askin A, Besiroglu L, Tosun A. Is high-frequency repetitive transcranial magnetic stimulation of the left primary motor cortex superior to the stimulation of the left dorsolateral prefrontal cortex in fibromyalgia syndrome? Somatosensory & Motor Research. 2019;36(1):56–62.30955403
52 Bilir B, Askin A, Sengul I, Tosun A. Effects of high frequency neuronavigated repetitive transcranial magnetic stimulation in fibromyalgia syndrome: A double-blinded, randomized controlled study. American Journal of Physical Medicine & Rehabilitation. 2020;20:20.
53 Cheng CM, Wang SJ, Su TP, . Analgesic effects of repetitive transcranial magnetic stimulation on modified 2010 criteria-diagnosed fibromyalgia: Pilot study. Psychiatry & Clinical Neurosciences. 2019;73(4):187–193.30588705
54 Fitzgibbon BM, Hoy KE, Knox LA, . Evidence for the improvement of fatigue in fibromyalgia: A 4-wk left dorsolateral prefrontal cortex repetitive transcranial magnetic stimulation randomized-controlled trial. European Journal of Pain. 2018;22(7):1255–1267.29542208
55 Guinot M, Maindet C, Hodaj H, . Effects of repetitive transcranial magnetic stimulation and multicomponent therapy in patients with fibromyalgia: a randomized controlled trial. Arthritis care & research. 2019;30:30.
56 Mattoo B, Tanwar S, Bhatia R, Tripathi M, Bhatia R. Repetitive transcranial magnetic stimulation in chronic tension-type headache: A pilot study. Indian Journal of Medical Research. 2019;150(1):73–80.
57 Sahu AK, Sinha VK, Goyal N. Effect of adjunctive intermittent theta-burst repetitive transcranial magnetic stimulation as a prophylactic treatment in migraine patients: A double-blind sham-controlled study. Indian Journal of Psychiatry. 2019;61(2):139–145.30992607
58 Ahmadizadeh MJ, Rezaei M. Unilateral right and bilateral dorsolateral prefrontal cortex transcranial magnetic stimulation in treatment post-traumatic stress disorder: A randomized controlled study. Brain Research Bulletin. 2018;140:334–340.29883597
59 Fryml LD, Pelic CG, Acierno R, . Exposure Therapy and Simultaneous Repetitive Transcranial Magnetic Stimulation: A Controlled Pilot Trial for the Treatment of Posttraumatic Stress Disorder. Journal of ECT. 2019;35(1):53–60.
60 Isserles M, Shalev AY, Roth Y, . Effectiveness of deep transcranial magnetic stimulation combined with a brief exposure procedure in post-traumatic stress disorder--a pilot study. Brain Stimulation. 2013;6(3):377–383.22921765
61 Kozel FA, Motes MA, Didehbani N, . Repetitive TMS to augment cognitive processing therapy in combat veterans of recent conflicts with PTSD: A randomized clinical trial. Journal of Affective Disorders. 2018;229:506–514.29351885
62 Kozel FA, Van Trees K, Larson V, . One hertz versus ten hertz repetitive TMS treatment of PTSD: A randomized clinical trial. Psychiatry Research. 2019;273:153–162.30641346
63 Leong K, Chan P, Ong L, . A Randomized Sham-controlled Trial of 1-Hz and 10-Hz Repetitive Transcranial Magnetic Stimulation (rTMS) of the Right Dorsolateral Prefrontal Cortex in Civilian Post-traumatic Stress Disorder. Canadian Journal of Psychiatry - Revue Canadienne de Psychiatrie. 2020:706743720923064.
64 Nam DH, Pae CU, Chae JH. Low-frequency, Repetitive Transcranial Magnetic Stimulation for the Treatment of Patients with Posttraumatic Stress Disorder: a Double-blind, Sham-controlled Study. Clinical Psychopharmacology & Neuroscience. 2013;11(2):96–102.24023554
65 Petrosino NJ, Wout-Frank MV, Aiken E, . One-year clinical outcomes following theta burst stimulation for post-traumatic stress disorder. Neuropsychopharmacology. 2020;45(6):940–946.31794974
66 Philip NS, Aiken EE, Kelley ME, Burch W, Waterman L, Holtzheimer PE. Synchronized transcranial magnetic stimulation for posttraumatic stress disorder and comorbid major depression. Brain Stimulation. 2019;12(5):1335–1337.31204205
67 Philip NS, Barredo J, Aiken E, . Theta-Burst Transcranial Magnetic Stimulation for Posttraumatic Stress Disorder. American Journal of Psychiatry. 2019;176(11):939–948.
68 Watts BV, Landon B, Groft A, Young-Xu Y. A sham controlled study of repetitive transcranial magnetic stimulation for posttraumatic stress disorder. Brain Stimulation. 2012;5(1):38–43.22264669
69 Choi GS, Kwak SG, Lee HD, Chang MC. Effect of high-frequency repetitive transcranial magnetic stimulation on chronic central pain after mild traumatic brain injury: A pilot study. Journal of Rehabilitation Medicine. 2018;50(3):246–252.29392332
70 Hoy KE, McQueen S, Elliot D, Herring SE, Maller JJ, Fitzgerald PB. A Pilot Investigation of Repetitive Transcranial Magnetic Stimulation for Post-Traumatic Brain Injury Depression: Safety, Tolerability, and Efficacy. Journal of Neurotrauma. 2019;36(13):2092–2098.30712461
71 Lee SA, Kim MK. Effect of Low Frequency Repetitive Transcranial Magnetic Stimulation on Depression and Cognition of Patients with Traumatic Brain Injury: A Randomized Controlled Trial. Medical Science Monitor. 2018;24:8789–8794.30513530
72 Leung A, Fallah A, Shukla S, . rTMS in Alleviating Mild TBI Related Headaches--A Case Series. Pain Physician. 2016;19(2):E347–354.26815263
73 Leung A, Metzger-Smith V, He Y, . Left Dorsolateral Prefrontal Cortex rTMS in Alleviating MTBI Related Headaches and Depressive Symptoms. Neuromodulation. 2018;21(4):390–401.28557049
74 Manko G, Olszewski H, Krawczynski M, Tlokinski W. Evaluation of differentiated neurotherapy programs for patients recovering from severe TBI and long term coma. Acta Neuropsychologica. 2013;11(1):9–18.
75 Neville IS, Zaninotto AL, Hayashi CY, . Repetitive TMS does not improve cognition in patients with TBI: A randomized double-blind trial. Neurology. 2019;93(2):e190–e199.31175209
76 Rao V, Bechtold K, McCann U, . Low-Frequency Right Repetitive Transcranial Magnetic Stimulation for the Treatment of Depression After Traumatic Brain Injury: A Randomized Sham-Controlled Pilot Study. Journal of Neuropsychiatry & Clinical Neurosciences. 2019;31(4):306–318.
77 Siddiqi S, Trapp N, Hacker C, . Repetitive Transcranial Magnetic Stimulation with Resting-State Network Targeting for Treatment-Resistant Depression in Traumatic Brain Injury: a Randomized, Controlled, Double-Blinded Pilot Study. Journal of neurotrauma. 2019;36(8):1361–1374.30381997
78 Stilling J, Paxman E, Mercier L, . Treatment of Persistent Post-Traumatic Headache and Post-Concussion Symptoms Using Repetitive Transcranial Magnetic Stimulation: A Pilot, Double-Blind, Randomized Controlled Trial. Journal of Neurotrauma. 2020;37(2):312–323.31530227
79 Liu X, Zhao X, Liu T, . The effects of repetitive transcranial magnetic stimulation on cue-induced craving in male patients with heroin use disorder. EBioMedicine. 2020;56:102809.32512513
80 Shen Y, Cao X, Tan T, . 10-Hz Repetitive Transcranial Magnetic Stimulation of the Left Dorsolateral Prefrontal Cortex Reduces Heroin Cue Craving in Long-Term Addicts. Biological Psychiatry. 2016;80(3):e13–14.26995024
81 Mrabet H, Mrabet A, Hattab N, Manai R, Zouari B. Repetitive transcranial magnetic stimulation as a treatment for chronic pain: A Tunisian series. Neurophysiologie Clinique. 2019;49(3):249–250.30711433
82 Lawson McLean A, Frank S, Zafar N, Waschke A, Kalff R, Reichart R. Time course of the response to navigated repetitive transcranial magnetic stimulation at 10 Hz in chronic neuropathic pain. Neurological Research. 2018;40(7):564–572.29583099
83 Hodaj H, Payen JF, Hodaj E, . Long-term treatment of chronic orofacial, pudendal, and central neuropathic limb pain with repetitive transcranial magnetic stimulation of the motor cortex. Clinical Neurophysiology. 2020;131(7):1423–1432.32387962
84 Pinot-Monange A, Moisset X, Chauvet P, . Repetitive Transcranial Magnetic Stimulation Therapy (rTMS) for Endometriosis Patients with Refractory Pelvic Chronic Pain: A Pilot Study. Journal of Clinical Medicine. 2019;8(4):13.
85 Nikkola J, Holm A, Seppanen M, Joutsi T, Rauhala E, Kaipia A. Repetitive Transcranial Magnetic Stimulation for Chronic Prostatitis/Chronic Pelvic Pain Syndrome: A Prospective Pilot Study. International neurourology journal. 2020;24(2):144–149.32615676
86 Carpenter LL, Conelea C, Tyrka AR, . 5Hz Repetitive transcranial magnetic stimulation for posttraumatic stress disorder comorbid with major depressive disorder. Journal of Affective Disorders. 2018;235:414–420.29677606
87 Taghva A, Silvetz R, Ring A, . Magnetic Resonance Therapy Improves Clinical Phenotype and EEG Alpha Power in Posttraumatic Stress Disorder. Trauma Monthly. 2015;20(4):e27360.26839865
88 Oznur T, Akarsu S, Celik C, . Is transcranial magnetic stimulation effective in treatment-resistant combat related posttraumatic stress disorder? Neurosciences. 2014;19(1):29–32.24419446
89 Woodside DB, Colton P, Lam E, Dunlop K, Rzeszutek J, Downar J. Dorsomedial prefrontal cortex repetitive transcranial magnetic stimulation treatment of posttraumatic stress disorder in eating disorders: An open-label case series. International Journal of Eating Disorders. 2017;50(10):1231–1234.
90 Philip NS, Ridout SJ, Albright SE, Sanchez G, Carpenter LL. 5-Hz Transcranial Magnetic Stimulation for Comorbid Posttraumatic Stress Disorder and Major Depression. Journal of Traumatic Stress. 2016;29(1):93–96.26748883
91 Nursey J, Sbisa A, Knight H, . Exploring Theta Burst Stimulation for Post-traumatic Stress Disorder in Australian Veterans-A Pilot Study. Military Medicine. 2020;30:30.
92 Seagly KS. PTSD symptom severity and neurocognitive performance as a function of combined TMS and imaginal exposure in OIF/OEF combat veterans with treatment resistant PTSD. Dissertation Abstracts International: Section B: The Sciences and Engineering. 2016;77(3-B(E).
93 Koski L, Kolivakis T, Yu C, Chen JK, Delaney S, Ptito A. Noninvasive brain stimulation for persistent postconcussion symptoms in mild traumatic brain injury. Journal of Neurotrauma. 2015;32(1):38–44.24955920
94 Shimizu T, Hosomi K, Maruo T, . Efficacy of deep rTMS for neuropathic pain in the lower limb: a randomized, double-blind crossover trial of an H-coil and figure-8 coil. Journal of Neurosurgery. 2017;127(5):1172–1180.28156250