# Evidence Brief: Intracameral Moxifloxacin for Prevention of Endophthalmitis After Cataract Surgery

## PREFACE

The VA Evidence Synthesis Program (ESP) was established in 2007 to provide timely and accurate syntheses of targeted health care topics of importance to clinicians, managers, and policymakers as they work to improve the health and health care of Veterans. These reports help:

- Develop clinical policies informed by evidence;
- Implement effective services to improve patient outcomes and to support VA clinical practice guidelines and performance measures; and
- Set the direction for future research to address gaps in clinical knowledge.

The program comprises four ESP Centers across the US and a Coordinating Center located in Portland, Oregon. Center Directors are VA clinicians and recognized leaders in the field of evidence synthesis with close ties to the AHRQ Evidence-based Practice Center Program. The Coordinating Center was created to manage program operations, ensure methodological consistency and quality of products, interface with stakeholders, and address urgent evidence needs. To ensure responsiveness to the needs of decision-makers, the program is governed by a Steering Committee composed of health system leadership and researchers. The program solicits nominations for review topics several times a year via the program website (https://www.hsrd.research.va.gov/publications/esp/TopicNomination.cfm).

The present report was developed in response to a request from VHA Ophthalmology Program Office. The scope was further developed with input from Operational Partners (below) and the ESP Coordinating Center review team.

## ACKNOWLEDGMENTS

The authors are grateful to Kathryn Vela, MLIS for literature searching, Payten Sonnen for data editorial and citation management support, and the following individuals for their contributions to this project:

### Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Amy Chomsky, MD
  Chief of Ophthalmology
  VA Tennessee Valley Healthcare System
- Glenn Cockerham, MD
  National Director
  VHA Ophthalmology Program Office

## EXECUTIVE SUMMARY

#### Background

The Evidence Synthesis Program Coordinating Center is responding to a request from the VHA Ophthalmology Program Office for an Evidence Brief on intracameral moxifloxacin for preventing endophthalmitis after cataract surgery. Findings from this Evidence Brief will be used to inform VA clinical practice and related policy on intracameral moxifloxacin use for preventing endophthalmitis after cataract surgery.

#### Methods

To identify studies, we searched MEDLINE®, Cochrane Database of Systematic Reviews, CINAHL, and other sources up to January 2022. We used prespecified criteria for study selection, data abstraction, and rating internal validity and strength of the evidence. See the Methods section and our PROSPERO protocol for full details of our methodology.

Key Findings

- Intracameral moxifloxacin use is associated with a 73% reduction in odds of endophthalmitis compared to standard care (OR = 0.27, 95% CI [0.19, 0.40], p < .0001), based on a meta-analysis of 14 comparative studies of 3,566,022 eyes.
- Intracameral moxifloxacin appears to be safe at the dosages and preparations reported, with no studies reporting adverse events directly related to moxifloxacin use.
- Odds of endophthalmitis after cataract surgery did not significantly differ with use of intracameral moxifloxacin compared to intracameral cefuroxime (OR = 1.34, 95 CI [0.73, 2.45], p = 0.25), based on a meta-analysis of 5 comparative studies of 847,070 eyes.
- Rigorous studies conducted in US settings may increase support for broadening use of intracameral moxifloxacin in place of or alongside topical antibiotics.
- Consistent policies, procedures, and access to standardized preparations of moxifloxacin for intracameral use are important for expanding use of intracameral moxifloxacin within the VHA.

Endophthalmitis is a rare, serious infection of the eye that can lead to permanent loss of vision. Topical antibiotic eyedrops are often prescribed to prevent endophthalmitis after cataract surgery. However, efficacy of topical drops is unclear, and there are also concerns about patient adherence to regular use of drops in the postsurgical period. In contrast to topical drops, intracameral antibiotics are administered only once (at the end of the surgical procedure after intraocular lens insertion). Prior studies have found that several antibiotics available for intracameral delivery, including cefuroxime, vancomycin, and moxifloxacin, may be beneficial for preventing endophthalmitis when delivered intracamerally. Due to concerns around antibiotic resistance and potential adverse events from use of cefuroxime and vancomycin, moxifloxacin has more recently been investigated.

Outside of the United States, moxifloxacin and other antibiotics are commercially available and commonly used in intracameral applications. Although US surgeons also routinely administer intracameral antibiotics, there are currently no antibiotics that are approved by the US Food and Drug Administration for intraocular use, and US surgeons must use repackaged and diluted topical or injectable solutions off-label. Increased risk, liability, and logistical challenges of using antibiotics off-label has led to less intracameral antibiotic use in the US compared to other countries where commercial intracameral formulations are available. Within the VHA, limited access to intracameral antibiotics has led to irregular and inconsistent usage across VHA facilities. Although several meta-analyses have reported prophylactic benefit of intracameral moxifloxacin, new evidence has emerged since the publication of these reviews. This report synthesizes the available evidence on benefits and harms of intracameral moxifloxacin for preventing endophthalmitis after cataract surgery, with the aim of informing VHA clinical practice.

Among 21 included studies, 14 examined intracameral moxifloxacin for preventing endophthalmitis and reported occurrence of endophthalmitis after surgery (total eyes = 3,566,022). A meta-analysis of study results found that intracameral moxifloxacin use is associated with a 73% reduction in odds of endophthalmitis compared to standard care (OR = 0.27, 95% CI [0.19, 0.40], p < .0001). Standard care commonly included pre-, intra-, and/or postoperative use of povidone iodine with postoperative topical antibiotics and/or corticosteroids regularly used across intervention and comparator groups. Pooling results of 5 studies reporting comparative effectiveness of intracameral moxifloxacin versus intracameral cefuroxime (total eyes = 847,070); the odds of endophthalmitis did not significantly differ between antibiotic groups (OR = 1.34, 95 CI [0.73, 2.45], p = 0.25). Intracameral moxifloxacin also appears to be safe at the dosages and preparations reported in the studies, with no studies reporting adverse events directly related to moxifloxacin use.

These findings align with previous systematic reviews, even with the addition of 9 studies not included in previous reviews, suggesting that these results are relatively stable. However, the studies are limited by study design and study methodology. Only 1 randomized controlled trial (RCT) reported on endophthalmitis rates among the 21 included studies, and the observational studies often compared surgeries before and after introduction of intracameral moxifloxacin as a standard for endophthalmitis prophylaxis in their hospital or health system. Although most studies attempted to minimize differences between intervention groups by comparing surgeries done at a single center and/or by a single surgeon, patient and/or surgery characteristics were often unreported and may have differed after introduction of intracameral moxifloxacin. Lack of reporting and adjustment for potential confounders weakens our confidence in these findings.

Additionally, no studies were conducted in the VHA and only 4 studies were conducted within the US. Cataract surgery standards, procedures, and access to intracameral moxifloxacin vary among different countries and healthcare systems, and the available evidence may not be fully applicable to cataract surgery care in the US or VHA. Rigorous studies conducted in US settings may increase support for broader use of intracameral moxifloxacin in place of or alongside topical antibiotics, including by increasing the likelihood of FDA approval of intracameral moxifloxacin. Within the VHA, limited access to intracameral antibiotics has led to irregular and inconsistent usage across VHA facilities, and consistent policies, procedures, and access to standardized preparations of moxifloxacin for intracameral use are needed.

## INTRODUCTION

### PURPOSE

The Evidence Synthesis Program Coordinating Center (ESP CC) is responding to a request from the Veterans Health Administration (VHA) Ophthalmology Program Office for an Evidence Brief on intracameral moxifloxacin for preventing endophthalmitis after cataract surgery. Findings from this brief will be used to inform VHA clinical practice and related policy on intracameral moxifloxacin use for preventing endophthalmitis after cataract surgery.

### BACKGROUND

Endophthalmitis is a rare, serious infection of the eye causing inflammation and vision damage, and may lead to permanent vision loss.^1^ Cataract surgery is one of the most common causes of endophthalmitis, as bacteria can enter the eye from the patients’ eyelids, surgical instruments, and/or healthcare personnel during surgery.^2^ Although the rate of endophthalmitis after cataract surgery in the US is low at around 0.08% to 0.14%,^3,4^ the large number of cataract surgeries performed in the US and the poor visual prognosis for patients with endophthalmitis make it a serious concern.

Treatment of endophthalmitis involves systemic and locally injected antibiotics, and vitrectomy, a surgical removal of infected vitreous from the eye.^1,2^ Although early treatment of endophthalmitis may improve visual outcomes, the prognosis of endophthalmitis remains poor.^2^ Therefore, prevention of endophthalmitis after cataract surgery is essential to reduce the risk of poor visual outcomes. Prevention options include use of povidone iodine as a topical antiseptic, saline irrigation, and topical, oral, or injected antibiotics. Although povidone iodine is routinely used and widely accepted as a surgical antiseptic, risk of endophthalmitis remains and additional preventive measures are needed.^5,6^ Topical antibiotic eyedrops, commonly along with topical steroid drops, are often prescribed to prevent endophthalmitis after cataract surgery.^5,6^

The efficacy of topical drops depends upon patient adherence and correct administration technique, and tracking of patient adherence and administration is difficult.^7^ Barriers to proper administration and compliance with topical eye drops include age, physical disability, complex drug regimens that may require administration of more than 1 type of eye drop (ie, topical antibiotics and topic steroids), and inexperience using eye drops.^8,9^ Topical eyedrop compliance may be a particular challenge among Veterans due to older age^10^ and higher rates of comorbidity and disability compared to the general population.^11^ In contrast to topical drops, intracameral antibiotics are administered only once (at the end of the surgical procedure after intraocular lens insertion).^4^

Intracameral antibiotics are widely used after cataract surgery to prevent endophthalmitis.^4^ Common antibiotics for intracameral delivery include cefuroxime, moxifloxacin, and vancomycin.^12^ In 2007, the European Association of Cataract and Refraction Surgeons (ESCRS) published a randomized controlled trial (RCT) showing effectiveness of intracameral injection of cefuroxime compared to topical antibiotics.^13^ However, concerns around antibiotic resistance and adverse effects, including toxic anterior segment syndrome (TASS), a severe acute intraocular inflammation, have led to reduced use of cefuroxime.^12,14^ Similarly, vancomycin is used infrequently due to cases of vancomycin-associated hemorrhagic occlusive retinal vasculitis.^14–16^ Moxifloxacin has more recently been explored to overcome the issues of antibiotic resistance and potential adverse effects, and studies have found that moxifloxacin may be beneficial for preventing endophthalmitis when delivered intracamerally after cataract surgery (compared to topical or no use of antibiotics).^14,16,17^ Potential toxic effects of intracameral moxifloxacin, including endothelial cell damage and TASS, have been reported at higher doses (above 0.5 mg/mL),with the use of specific inactive ingredients (xanthan gum), and with the use of compounded moxifloxacin formulations.^18^ However, intracameral moxifloxacin doses of up to 0.5 mg/0.1 mL without preservatives have been reported to be safe with no adverse effects.^15^

Intracameral antibiotics are commercially available outside of the US. However, although the American Academy of Ophthalmology has stated that there are multiple benefits to use of intracameral antibiotics after cataract surgery,^15^ there are currently no antibiotics approved by the US Food and Drug Administration (FDA) for intracameral endophthalmitis prophylaxis. US cataract surgeons routinely administer intracameral antibiotics, but rely on the off-label use of topical antibiotics, which must be repackaged and diluted for intracameral injection.^15^ Using antibiotics off-label for intracameral injection can pose increased risks due to errors in compounding and dilution of topical solutions, and potential adverse effects from inactive ingredients not intended for intracameral use. Due to the increased risk, liability, and logistical challenges of using antibiotics off-label, intracameral antibiotics are less widely used in the US compared to other countries where commercial intracameral formulations are available.^19^ Within the VHA, limited access to antibiotics for intracameral use has led to irregular and inconsistent usage across VHA facilities. Cataract surgery is the most frequently performed surgery in the VHA, with nearly 70,000 cataract surgeries performed in fiscal year 2017,^20^ and there is a need for consistent usage and preparation across VHA facilities and pharmacies.

Although several meta-analyses^14,16,17^ have reported prophylactic benefit of intracameral moxifloxacin, new evidence has emerged since the publication of these reviews. This report synthesizes the available evidence on benefits and harms of intracameral moxifloxacin for preventing endophthalmitis after cataract surgery, with the aim of informing VHA clinical practice.

## METHODS

### PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42022308908).

### KEY QUESTIONS

The following key questions (KQs) were the focus of this review:

KQ 1 What are the benefits and harms of intracameral moxifloxacin use during cataract surgery to prevent postoperative endophthalmitis?
KQ 2 How do benefits and harms of intracameral moxifloxacin use during cataract surgery vary based on administration method (eg, diluted vs undiluted) and use of co-interventions (eg, with vs without topical antibiotic eye drops)?

### ELIGIBILITY CRITERIA

The ESP included studies that met the following criteria:

Population | Adults undergoing cataract surgery
Intervention | Intracameral moxifloxacin use during cataract surgery
Comparator | Care as usual (ie, no intracameral antibiotic use during cataract surgery)
Outcomes | Incidence of postoperative endophthalmitis, harms (eg, corneal edema, severe inflammation, retinal toxicity/vasculitis), patient quality of life, patient use of co-interventions (eg, topical antibiotic eye drops)
Timing | Any
Setting | Any
Study Design | Any, but we may prioritize articles using a best-evidence approach to accommodate Evidence Brief timeline

### DATA SOURCES AND SEARCHES

To identify articles relevant to the key questions, a research librarian searched Ovid MEDLINE, CINAHL, Cochrane Database of Systematic Reviews, and ClinicalTrials.gov, as well as the AHRQ and HSR&D databases from 2016 through January 2022 using terms for moxifloxacin and cataract surgery (see Appendix A in Supplemental Materials for complete search strategies). We utilized several existing systematic reviews^14,16,17^ to identify citations published prior to 2016. We limited the search to published and indexed articles involving human subjects available in the English language. Study selection was based on the eligibility criteria described above. Titles, abstracts, and full-text articles were reviewed by 1 investigator and checked by another. All disagreements were resolved by consensus or discussion with a third reviewer.

### DATA ABSTRACTION AND ASSESSMENT

Effect information and population, intervention, and comparator characteristics were abstracted from all included studies. The internal validity (risk of bias) of each included study was rated using the Cochrane risk of bias tools.^21,22^ All data abstraction and internal validity ratings were first completed by 1 reviewer and then checked by another; disagreements were resolved by consensus or discussion with a third reviewer. We graded the strength of the evidence for each outcome based on the AHRQ Methods Guide for Comparative Effectiveness Reviews.^23^ This approach provides a rating of confidence in reported findings based on trial methodology (design, quality, and risk of bias), consistency (whether effects are in the same direction and have a consistent magnitude), precision, and directness (whether assessed outcomes are clinically important to patients and providers). For this review, we applied the following general algorithm: high strength evidence consisted of multiple, large trials with low risk of bias, consistent and precise findings, and clinically relevant outcomes; moderate strength evidence consisted of multiple trials with low to unclear risk of bias, consistent and precise findings, and clinically relevant outcomes; low strength evidence consisted of a single trial, or multiple small trials, with unclear to high risk of bias, inconsistent or imprecise findings, and/or outcomes with limited clinical relevance; and insufficient evidence consisted of a single trial with unclear or high risk of bias, or no available trials.

### SYNTHESIS

Evidence on antibiotic-related adverse events was synthesized narratively due to inconsistency in measurement and reporting of these outcomes. For endophthalmitis rates, we quantitatively synthesized evidence using statistical methods appropriate for rare outcomes. For main and moderator analyses, we employed random-effects hypergeometric-normal models^24–26^ to estimate effect sizes and their precision directly from count information. Moderator (mixed-effects) analyses examined whether overall effect estimates differed by surgery type. We carried out sensitivity analyses using a random-effects extension of the Peto method,^24^ which is an approach intended for the analysis of rare events. Meta-analyses were conducted using the metafor^27^ package for R (R Foundation for Statistical Computing, Vienna, Austria).

All included studies reporting endophthalmitis occurrence after intracameral moxifloxacin or standard care did so using count information, and effects are represented using odds ratios (ORs). ORs reported for sensitivity analyses were calculated using the Peto method. To increase interpretability of findings, we also estimated risk difference (RD) after intracameral moxifloxacin using a traditional random-effects model. Precision of study-level and overall estimates is reported using 95% confidence intervals (CIs), and CIs were used to evaluate statistical significance of overall estimates at a significance level of .05. For main and moderator analyses, exact CIs were calculated based on the hypergeometric-normal distribution; cluster-robust (sandwich) CIs with small-sample adjustment were employed in sensitivity analyses using the Peto method and in models estimating risk difference. Heterogeneity was estimated using maximum-likelihood estimation and is presented as 95% prediction intervals (PIs). One included study^28^ reported no endophthalmitis events; to facilitate inclusion of this study in analyses, 0.5 was added to each of the study’s counts. Sensitivity analyses based on the Peto method did not require this continuity correction, and we also report the main analysis with this study excluded to gauge sensitivity of our findings to the correction. No syntheses included dependent estimates (ie, multiple estimates from the same study in the same analysis/subgroup).

## RESULTS

### LITERATURE FLOW

The literature flow diagram (Figure 2) summarizes the results of the study selection process (full list of excluded studies available in Appendix B in Supplemental Materials).

Figure 1 Literature Flowchart

Abbreviations. CINAHL=Cumulative Index to Nursing and Allied Health Literature.

### LITERATURE OVERVIEW

Our search identified 169 potentially relevant articles. We included 21 studies^28–48^ which are summarized in Table 1 (see Appendix C in Supplemental Materials for full study details). Two studies^40,46^ were RCTs, and the remaining studies were observational cohorts. Although most studies were designed to evaluate the efficacy of moxifloxacin for prevention of endophthalmitis, 5 studies^30,44–46,48^ focused on the safety of moxifloxacin use. Two of these studies reported no endophthalmitis events,^45,48^ while the others did not directly report endophthalmitis rates. We also identified 3 underway studies (see Appendix D in Supplemental Materials) examining intracameral moxifloxacin for endophthalmitis prophylaxis, 2 of which are RCTs.

Most studies compared intracameral moxifloxacin use to standard care without intracameral antibiotic. Standard care usually included pre-, intra-, and/or postoperative use of povidone iodine with postoperative topical antibiotics and/or corticosteroids given to all patients (intervention and comparator groups), although some studies reported varied topical antibiotic use per institution or at surgeon discretion. Several studies included comparisons to both standard care and intracameral cefuroxime,^29,31,33^ while 2 studies compared intracameral moxifloxacin to intracameral cefuroxime only with no comparison to standard care.^36,42^ The majority of studies were conducted outside of the US, with only 4 studies^33,42,44,46^ conducted within the US. The median number of eyes examined was 40,392 (range 57 to 2,062,643). Almost all studies (N = 19) utilized phacoemulsification (PE) cataract surgery, with some studies also including manual small incision cataract surgery (MSCIS) or extracapsular cataract extraction (ECCE). Intracameral antibiotic dosage was commonly 0.5 mg in 0.1 mL of 0.5% moxifloxacin.

Only 2 studies were RCTs, 1 of which appeared to be well conducted,^40^ while the other^46^ lacked information on the randomization and allocation processes, had unclear blinding of patients, and excluded more than 15% of the initially randomized population due to loss to follow-up or adverse events unrelated to the study. Most of the observational studies examined cataract surgeries conducted within a single time period during which intracameral moxifloxacin was introduced and compared surgeries before and after the introduction of intracameral moxifloxacin. Common methodological limitations of the observational studies included lack of information on baseline patient and surgery characteristics, lack of adjustment for potential confounders, and unclear level and/or handling of missing data. Several studies had more severe methodological limitations, including comparison of data from different centers or time periods with no information or accounting for potential differences between groups, lack of adjustment for known confounders, and unclear intervention assignment (ie, unclear why certain patients received intracameral moxifloxacin and others did not).

Table 1 Characteristics of Included Studies

Study; Study design | Sample Size; Follow-up | Surgery Type | Moxifloxacin Concentration and Preparation | Comparator | Topical Antibiotic Use^*^ | Outcomes Assessed
Arshinoff, 2011^29^; Retrospective Cohort | N=104,914; NR | PE | Variable across surgical centers (0.1 to 0.5 mg MOX per 01. to 0.2 mL) | No IC antibiotic or IC cefuroxime | NR | Endophthalmitis rate
Bhatta, 2021^37^,^†^; Retrospective Cohort | N=11,983; 6 weeks | PE or MSICS | 0.5 mg MOX in 0.1 mL | No IC antibiotic | All patients | Endophthalmitis rate, TASS, adverse events
Cetinkaya, 2015^45^; Retrospective Cohort | N=65; 1 year | PE | 0.1 mL of undiluted 0.5% MOX | No IC antibiotic | All patients | Corneal edema, TASS
Dave, 2022^34^,^†^; Retrospective Cohort | N=66,967; 6 weeks | PE, MSICS, or ECCE | 0.5 mg MOX in 0.1 mL | No IC antibiotic | All patients | Endophthalmitis rate, corneal edema, adverse events
Ekinci, 2012^30^; Retrospective Cohort | N=60; 3 days | PE | 0.1 mL of undiluted 0.5% MOX | No IC antibiotic | All patients | Corneal edema, adverse events
Frilling, 2013^31^; Retrospective Cohort | N=464,755; 4 weeks | PE or “other”^**^ | Variable across surgical centers | No IC antibiotic or IC cefuroxime | Varied | Endophthalmitis rate
Galvis, 2014^28^; Retrospective Cohort | N=2,674; 2 weeks | PE | 0.05 mL of undiluted 0.5% MOX | No IC antibiotic | All patients | Endophthalmitis rate
Haripriya, 2016^38^,^†^; Retrospective Cohort | N=75,937; 6 weeks | PE, MSICS, or ECCE | 0.5 mg in 0.1 mL of 0.5% MOX | No IC antibiotic | All patients | Endophthalmitis rate, TASS, adverse events
Haripriya, 2017^32^; Retrospective Cohort | N=617,453; 6 weeks | PE, MSICS, or ECCE | 0.5 mg in 0.1 mL of 0.5% MOX | No IC antibiotic | All patients | Endophthalmitis rate, TASS, adverse events
Haripriya, 2019^39^,^†^; Retrospective Cohort | N=2,062,643; 6 weeks | PE, MSICS, or ECCE | 0.5 mg in 0.1 mL of 0.5% MOX | No IC antibiotic | All patients | Endophthalmitis rate, corneal edema, TASS, adverse events
Herrinton, 2016^33^; Retrospective Cohort | N=294,649; 3 months | PE | 0.25 mg MOX in 0.1 mL | No IC antibiotic or IC Cefuroxime | Varied | Endophthalmitis rate, macular edema, adverse events
Lane, 2008^46^; RCT | N=57; 3 months | PE | 0.25 mg in 0.05 mL of undiluted 0.5% MOX | Salt solution injection | All patients | Corneal edema, TASS, adverse events
Matsuura, 2013^47^; Retrospective Cohort | N=34,755; 1 month | PE | Varied among institutions (0.05 mg/mL to 0.5 mg/mL MOX) | No IC antibiotic | NR | Endophthalmitis rate, TASS, adverse events
Matsuura, 2014^48^; Retrospective Cohort | N=138; 3 months | PE | 0.15 mg/mL to 0.5 mg/mL of 0.5% MOX | Salt solution irrigation | All patients | TASS, adverse events
Melega, 2019^40^; RCT | N=3,640; 6 weeks | PE | 0.15 mg in 0.03 mL of undiluted 0.5% MOX | No IC antibiotic | All patients | Endophthalmitis rate, adverse events
Porwal, 2021^35^,^†^; Retrospective Cohort | N=40,392; NR | MSICS | NR | No IC antibiotic | NR | Endophthalmitis rate
Rathi, 2021^36^,^†^; Prospective Cohort | N=42,466; 11 weeks | PE or MSICS | 0.1 mL of 0.5% MOX | IC Cefuroxime | Varied | Endophthalmitis rate, corneal edema, TASS, adverse events
Shenoy, 2021^41^,^†^; Retrospective Cohort | N=214,782; 6 months | PE or MSICS | 0.1 mL of 0.5% MOX | No IC antibiotic | All patients | Endophthalmitis rate
Shorstein, 2021^42^,^†^; Retrospective Cohort | N=204,655; 3 months | NR | 0.1 mL - 1 mL of 0.1% MOX | IC Cefuroxime | Varied | Endophthalmitis rate
Viera, 2017^43^; Retrospective Cohort | N=7,195; 6 weeks | PE | 0.05 mL of MOX-hydrochloride at 5.45 mg/mL | No IC antibiotic | All patients | Endophthalmitis rate
Zhou, 2016^44^,^†^; Retrospective Cohort | N=222; 1 month | PE | 0.5 mg in 0.1 mL of 0.5% MOX | Topical MOX | Control group only | Corneal edema, macular edema, adverse events

Notes. Sample size is the number of eyes reported in each study.

* Postoperative topical antibiotic use classified as: all patients received topical antibiotics, only control patients received topical antibiotics, and topical antibiotic use varied among included patients (ie, at surgeon discretion).

** ”Other” surgery not specified in the study.

† Study not included in previous systematic reviews Huang 2016, Bowen 2018, and/or Wang 2020.

Abbreviations. ECCE=Extracapsular cataract extraction; IC=Intracameral, mg=milligram; MOX=moxifloxacin; mL=milliliter; MSICS=Manual Small Incision cataract surgery; NR=Not reported; PE=Phacoemulsification; TASS=Toxic anterior segment syndrome.

### INTRACAMERAL MOXIFLOXACIN TO PREVENT ENDOPHTHALMITIS

Pooling estimates from 1 RCT and 13 cohorts (N = 3,566,022 eyes; Figure 2) indicates that intracameral moxifloxacin use is associated with a 73% reduction in odds of endophthalmitis compared to standard care (OR = 0.27, 95% CI [0.19, 0.40], p < .0001), corresponding to approximately 7 fewer cases of endophthalmitis per 10,000 eyes (RD = −0.0007, 95% CI [−0.0009, −0.0004], p < .0001). This estimate did not meaningfully differ when removing 1 study for which a continuity correction was necessary (OR = 0.28, 95% CI [0.19, 0.41]) or when data were pooled using the Peto method (OR_Peto_ = 0.34, 95% CI [0.26, 0.45]). Heterogeneity was limited (95% PI [0.10, 0.75]), suggesting that future studies would likely find substantively similar results (ie, reduced occurrence of endophthalmitis with intracameral moxifloxacin use). Similar to the overall results, the 1 included RCT^40^ reported significantly lower incidence of endophthalmitis within 6 weeks of surgery among patients receiving moxifloxacin (1 of 1,818 eyes [0.05%], compared to 7 of 1,822 eyes [0.38%] in the topical eyedrop-only group; p = .04).

Figure 2 Occurrence of Endophthalmitis After Intracameral Moxifloxacin or Standard Care

Notes. Odds ratio for Galvis 2014 calculated with 0.5 added to all counts. Gray bars around summary estimate (diamond) represent 95% prediction interval.

Abbreviations. CI=confidence interval; Ctr=control group; Endop=endophthalmitis; Tx=treatment group.

We also identified 2 small studies^45,48^ (N = 203 eyes) that did not aim to assess the prophylactic benefit of intracameral moxifloxacin, but reported on occurrence of endophthalmitis among other adverse effects of cataract surgery. Both of these studies reported no instances of endophthalmitis among participants regardless of intracameral antibiotic use. Additionally, 5 studies^29,31,33,36,42^ (N = 847,070 eyes) reported comparative effectiveness of intracameral moxifloxacin versus intracameral cefuroxime; when pooled, odds of endophthalmitis did not significantly differ between antibiotic groups (OR = 1.34, 95 CI [0.73, 2.45], p = 0.25; OR_Peto_ = 1.34, 95% CI [0.84, 2.16]). Finally, odds of endophthalmitis after intracameral moxifloxacin or standard care did not appear to meaningfully differ by surgery type (p = .54; Figure 3).

Overall, we have moderate confidence in these findings as they are consistent, precise, and direct. The main limitation of the evidence is study design and methodological limitations of the studies, including lack of information on baseline patient and surgery characteristics, lack of adjustment for potential confounders, and unclear level and/or handling of missing data.

No studies specifically examined the effect of administration method (eg, diluted vs undiluted) or use of co-interventions (eg, with vs without topical antibiotic eye drops) on the efficacy of intracameral moxifloxacin.

Figure 3 Occurrence of Endophthalmitis After Intracameral Moxifloxacin or Standard Care by Surgery Type

Notes. Odds ratio for Galvis 2014 calculated with 0.5 added to all counts.

Abbreviations. CI=confidence interval; Ctr=control group; ECCE=extracapsular cataract extraction; Endop=endophthalmitis; MSICS=manual small incision cataract surgery; PE=phacoemulsification; Tx=treatment group.

### ADVERSE EFFECTS OF MOXIFLOXACIN USE

Intracameral moxifloxacin use appears to be safe at the dosages and preparations reported, with few adverse events reported and none reported as directly related to intracameral antibiotic use. A single study^46^ reported 2 cases of TASS with moxifloxacin use. The cases of TASS were discovered to be a part of a systemwide TASS epidemic (which included patients not enrolled in the study who did not receive intracameral moxifloxacin) due to use of reusable cannulas, which resolved after switching to disposable cannulas. Eight other studies^32,36–39,45,47,48^ reporting TASS outcome reported no cases of TASS among included participants. No other adverse reactions to moxifloxacin were reported.

Several studies^30,33,34,36,39,44–46^ reported on corneal or macular edema, which can occur as an adverse event of cataract surgery. No differences in these outcomes were reported between control patients and those receiving intracameral moxifloxacin, suggesting that use of intracameral moxifloxacin does not impact the rate of other potential adverse outcomes of cataract surgery.

## DISCUSSION

Findings from this review indicate that intracameral moxifloxacin use is associated with a 73% reduction in odds of endophthalmitis compared to standard care (14 studies; OR = 0.27, 95% CI [0.19, 0.40], p < .0001). Given the low overall rate of postoperative endophthalmitis (0.08 to 0.14%), this corresponds to approximately 7 fewer cases of endophthalmitis per 10,000 eyes. Most studies utilized phacoemulsification cataract surgery, which is the preferred and most commonly performed type of cataract surgery.^49^ However, in cases of more severe disease or limited access to equipment, extracapsular cataract extraction or manual small incision cataract surgery are still performed.^49,50^ These types of surgery may have a higher risk for postoperative infection due to larger incisions and/or variation in manual surgical technique. However, in subgroup analyses, the reduction in odds of endophthalmitis after intracameral moxifloxacin did not appear to meaningfully differ by surgery type (p = .54), suggesting that intracameral moxifloxacin can be used across cataract surgery types.

When pooling the results of 5 studies^29,31,33,36,42^ reporting comparative effectiveness of intracameral moxifloxacin versus intracameral cefuroxime, odds of endophthalmitis after cataract surgery did not differ by antibiotic type (OR = 1.34, 95 CI [0.73, 2.45], p = 0.25). While both moxifloxacin and cefuroxime appear to be effective at reducing rates of endophthalmitis, concerns around antibiotic resistance and potential adverse effects of cefuroxime have led to increased use of moxifloxacin as an alternative.^15^ Although antibiotic resistance to moxifloxacin was not reported in any of the included studies, it should be considered as use of intracameral moxifloxacin expands.

Potential toxic effects of moxifloxacin have been reported at higher concentrations, with use of certain inactive ingredients in specific brands of moxifloxacin,^15^ and with some compounded moxifloxacin.^18^ However, none of the studies included in our review reported adverse events directly related to moxifloxacin use. A single study reported 2 cases of TASS, but these cases were determined to be a part of a hospital-wide outbreak stemming from the use of reusable cannulas.^46^ Most included studies utilized the moxifloxacin brands Vigamox or Auromox, which do not have concerns around preservative use, pH, or compounding that have been linked to adverse events. Intracameral moxifloxacin use appears to be safe at the dosages and intracameral preparations reported in the included studies, but it is important to consider potential adverse effects with varying dosages, brands, or compounding of moxifloxacin.

Findings from this review align with those reported in previous reviews (reduced odds of endophthalmitis with intracameral moxifloxacin use: OR range 0.20 to 0.30),^14,16,17^, even with the inclusion of 9 additional studies^34–39,41,42,44^ not included in the previous systematic reviews. This consistency with previously reported findings suggests that these results may be unlikely to change with future research. However, limitations in the evidence base weaken our confidence in these findings.

### LIMITATIONS

The main limitations of the evidence are study design and study methodology. Only 1 RCT^40^ reported on endophthalmitis rates among the 21 included studies. The observational studies often compared surgeries before and after introduction of intracameral moxifloxacin as a standard for endophthalmitis prophylaxis within a hospital or health system. Although most studies were done at a single center and/or by a single surgeon to minimize differences in surgery characteristics, the patient and/or surgery characteristics were often unreported and may have differed after introduction of intracameral moxifloxacin. A single study^33^ adjusted for potential confounders between groups, and differences between moxifloxacin and control groups in the other studies may have biased the results. Additionally, no studies were conducted in the VHA and only 4 studies were conducted within the US. In the US, topical or injectable antibiotics must be used off-label for intracameral use, and this may confer additional risk of potential adverse events. Thus, current evidence may not fully capture the potential for adverse events in settings without access to commercially available intracameral moxifloxacin. Cataract surgery standards and procedures may also differ between countries and healthcare systems and the available evidence may not be fully applicable to cataract surgery care in the US or VHA.

Limitations of our review methods include use of a second reviewer check for study selection, data abstraction, and risk of bias assessment rather than dual independent review, and use of existing systematic reviews to identify literature prior to 2016. However, the likelihood of missing relevant studies is low as we utilized several existing systematic reviews with comprehensive searches.

### FUTURE RESEARCH

Although existing research consistently shows prophylactic benefit of intracameral moxifloxacin, rigorous studies conducted in US settings may increase support for broader use of intracameral moxifloxacin in place of or alongside topical antibiotics. A triple blinded RCT^51^ is currently underway in the US examining use of intracameral moxifloxacin compared to placebo, and findings from this study may improve our confidence in the existing evidence. This study and further RCTs conducted in the US may also increase the likelihood of FDA approval of intracameral moxifloxacin, enabling more standardized use of intracameral moxifloxacin across the US and within the VHA. Expanded use of intracameral moxifloxacin as a standard of care without FDA approval may increase risk and liability challenges. Finally, most studies included the use of topical antibiotics in both intervention and control groups, and direct comparison of intracameral moxifloxacin to topical antibiotics was limited to a single study.^44^ Further studies directly comparing intracameral moxifloxacin alone to topical antibiotics are warranted.

### CONSIDERATIONS FOR USE OF INTRACAMERAL MOXIFLOXACIN IN VHA

Within the VHA, limited access to intracameral antibiotics has led to irregular and inconsistent usage across VHA facilities. In a 2016 survey of VHA ophthalmology chiefs, 33% reported use of intracameral antibiotics during cataract surgery (23% cefuroxime, 50% moxifloxacin, 18% vancomycin).^52^ Among those reporting no use of intracameral antibiotics, institutional and/or pharmacy difficulties was most often rated as the reason for non-use, followed by risk of dilution error, lack of evidence, risk of bacterial resistance, and risk of contamination.^52^ Given the concerns around patient adherence and correct administration of topical eye drops, particularly among Veterans who may have barriers to compliance such as older age and higher rates of comorbidity and disability,^10,11^ consistent policies and procedures for the use of intracameral antibiotics within the VHA are needed. However, variation in access to intracameral preparations of moxifloxacin across VHA sites creates challenges for consistent usage and concerns of increased risk from use of off-label compounded moxifloxacin. Availability of an FDA-approved intracameral antibiotic or standardized in-house preparation of intracameral moxifloxacin by the VHA pharmacy may be needed to enable standardized use.

### CONCLUSIONS

Intracameral moxifloxacin use is associated with substantially reduced odds of endophthalmitis compared to standard care. Additionally, intracameral moxifloxacin appears to be safe at the dosages and preparations reported in the included studies, with no reported adverse events related to moxifloxacin use. Available evidence may not be fully applicable to US or VHA healthcare settings, however, and future research with improved methodology and in US settings is warranted to inform standardized use of intracameral moxifloxacin within the VHA. Consistent usage of intracameral moxifloxacin across VHA sites is dependent upon consistent policies, procedures, and access to standardized intracameral preparations of moxifloxacin for intracameral use.

## REFERENCES

1 Durand ML. Endophthalmitis. Clinical Microbiology and Infection. 2013;19(3):227–234.23438028
2 Sheu S-J. Endophthalmitis. Korean Journal of Ophthalmology. 2017;31(4):283–289.28752698
3 Coleman A. How Big Data Informs Us About Cataract Surgery: The LXXII Edward Jackson Memorial Lecture. American Journal of Ophthalmology. 2015;160(6).
4 Javitt JC. Intracameral antibiotics reduce the risk of endophthalmitis after cataract surgery: does the preponderance of the evidence mandate a global change in practice? Ophthalmology. 2016;123(2):226–231.26802702
5 Peck TJ, Patel SN, Ho AC. Endophthalmitis after cataract surgery: an update on recent advances. Current Opinion in Ophthalmology. 2021;32(1):62–68.33196543
6 Haripriya A, Chang DF. Intracameral antibiotics during cataract surgery: evidence and barriers. Current Opinion in Ophthalmology. 2018;29(1):33–39.29095716
7 Novack GD, Caspar JJ. Peri-Operative Intracameral Antibiotics: The Perfect Storm? Journal of Ocular Pharmacology & Therapeutics. 2020;36(9):668–671.32580612
8 An JA, Kasner O, Samek DA, Lévesque V. Evaluation of eyedrop administration by inexperienced patients after cataract surgery. Journal of Cataract & Refractive Surgery. 2014;40(11).
9 Matossian C. Noncompliance with prescribed eyedrop regimens among patients undergoing cataract surgery—prevalence, consequences, and solutions. 2020.
10 VA Utilization Profile FY 2017. National Center for Veterans Analysis and Statistics. https://www.va.gov/vetdata/docs/Quickfacts/VA_Utilization_Profile_2017.pdf. Updated May 2020. Accessed April 19, 2022.
11 Holder KA. The disability of veterans. Washington, DC: US Census Bureau Social, Economic, and Housing Statistics Division. 2016.
12 Intracameral Medications Following Cataract Surgery. 2021;2022(March 29).
13 Group EES. Prophylaxis of postoperative endophthalmitis following cataract surgery: Results of the ESCRS multicenter study and identification of risk factors. Journal of Cataract & Refractive Surgery. 2007;33(6):978–988.17531690
14 Bowen RC, Zhou AX, Bondalapati S, . Comparative analysis of the safety and efficacy of intracameral cefuroxime, moxifloxacin and vancomycin at the end of cataract surgery: a meta-analysis. British Journal of Ophthalmology. 2018;102(9):1268–1276.29326317
15 American Academy of Ophthalmology, Hwang FS, Kim B, Pyun J. Intracameral Medications Following Cataract Surgery. https://eyewiki.aao.org/Intracameral_Medications_Following_Cataract_Surgery. Published 2021. Accessed March, 2022.
16 Huang J, Wang X, Chen X, Song Q, Liu W, Lu L. Perioperative Antibiotics to Prevent Acute Endophthalmitis after Ophthalmic Surgery: A Systematic Review and Meta-Analysis. PLoS ONE [Electronic Resource]. 2016;11(11):e0166141.
17 Wang XL, Huang XY, Wang Z, Sun W. The Anterior Chamber Injection of Moxifloxacin Injection to Prevent Endophthalmitis after Cataract Surgery: A Meta-analysis. Journal of ophthalmology. 2020;2020:7242969.32908685
18 US Food and Drug Administration. FDA alerts health care professionals of risks associated with intraocular use of compounded moxifloxacin. https://www.fda.gov/drugs/drug-safety-and-availability/fda-alerts-health-care-professionals-risks-associated-intraocular-use-compounded-moxifloxacin. Published 2020. Accessed March, 2022.
19 Javitt JC. Intracameral Antibiotics Reduce the Risk of Endophthalmitis after Cataract Surgery: Does the Preponderance of the Evidence Mandate a Global Change in Practice? American Academy of Ophthalmology. 2016.
20 Mudumbai S, Pershing S, Bowe T, . Variability and Costs of Low-Value Preoperative Testing for Cataract Surgery Within the Veterans Health Administration. JAMA Netw Open. 2021;4(5).
21 Sterne JA, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. Bmj. 2016;355:i4919.27733354
22 Higgins JP, Altman DG, Gøtzsche PC, . The Cochrane Collaboration’s tool for assessing risk of bias in randomised trials. Bmj. 2011;343:d5928.22008217
23 Berkman N, Lohr K, Ansari M, McDonagh M, Balk E, E. W. Methods Guide for Effectiveness and Comparative Effectiveness Reviews. AHRQ publication no. 13 (14)-EHC130-EF. 2013.
24 Jackson D, Law M, Stijnen T, Viechtbauer W, White IR. A comparison of seven random-effects models for meta-analyses that estimate the summary odds ratio. Stat Med. 2018;37(7):1059–1085.29315733
25 Stijnen T, Hamza TH, Ozdemir P. Random effects meta-analysis of event outcome in the framework of the generalized linear mixed model with applications in sparse data. Stat Med. 2010;29(29):3046–3067.20827667
26 van Houwelingen H, Zwinderman K, Stijnen T. A bivariate approach to meta-analysis. Stat Med. 1993;12:2273–2284.7907813
27 Viechtbauer W. metafor: Meta-analysis package for R. The Comprehensive R Archive Network. https://cran.r-project.org/web/packages/metafor/index.html. Published 2020. Accessed March, 2022.
28 Galvis V, Tello A, Sánchez MA, Camacho PA. Cohort study of intracameral moxifloxacin in postoperative endophthalmitis prophylaxis. Ophthalmol Eye Dis. 2014;6:1–4.24526838
29 Arshinoff SA, Bastianelli PA. Incidence of postoperative endophthalmitis after immediate sequential bilateral cataract surgery. J Cataract Refract Surg. 2011;37(12):2105–2114.22108106
30 Ekinci Koktekir B, Aslan BS. Safety of prophylactic intracameral moxifloxacin use in cataract surgery. J Ocul Pharmacol Ther. 2012;28(3):278–282.22304496
31 Friling E, Lundström M, Stenevi U, Montan P. Six-year incidence of endophthalmitis after cataract surgery: Swedish national study. J Cataract Refract Surg. 2013;39(1):15–21.23245359
32 Haripriya A, Chang DF, Ravindran RD. Endophthalmitis Reduction with Intracameral Moxifloxacin Prophylaxis: Analysis of 600 000 Surgeries. Ophthalmology. 2017;124(6):768–775.28214101
33 Herrinton LJ, Shorstein NH, Paschal JF, . Comparative Effectiveness of Antibiotic Prophylaxis in Cataract Surgery. Ophthalmology. 2016;123(2):287–294.26459998
34 Dave V, Singh V, Reddy J, Sharma S, Joseph J, Das T. Clinical features and microbiology of post-cataract surgery endophthalmitis with and without intracameral moxifloxacin prophylaxis: Endophthalmitis prophylaxis study report 3. Indian Journal of Ophthalmology. 2022;70(1):158–163.34937229
35 Porwal A, Patel A, Mathew B, . Incidence of postoperative endophthalmitis with and without use of intracameral moxifloxacin. In. Vol 68: Wolters Kluwer India Pvt Ltd; 2021:1353–1354.
36 Rathi V, Sharma S, Das T, Khanna R, Rathi VM, Khanna RC. Endophthalmitis prophylaxis study. Report 1: Intracameral cefuroxime and moxifloxacin prophylaxis for the prevention of postcataract endophthalmitis in rural India. Indian Journal of Ophthalmology. 2020;68(5):819–824.32317453
37 Bhatta S, Pant N, Poudel M. Postoperative endophthalmitis with and without intracameral moxifloxacin prophylaxis in a high volume surgery setting. BMJ Open Ophthalmology. 2021;6(1):e000609.
38 Haripriya A, Chang DF, Namburar S, Smita A, Ravindran RD. Efficacy of Intracameral Moxifloxacin Endophthalmitis Prophylaxis at Aravind Eye Hospital. Ophthalmology. 2016;123(2):302–308.26522705
39 Haripriya A, Chang DF, Ravindran RD. Endophthalmitis reduction with intracameral moxifloxacin in eyes with and without surgical complications: Results from 2 million consecutive cataract surgeries. Journal of Cataract & Refractive Surgery. 2019;45(9):1226–1233.31371152
40 Melega MV, Alves M, Cavalcanti Lira RP, . Safety and efficacy of intracameral moxifloxacin for prevention of post-cataract endophthalmitis: Randomized controlled clinical trial. Journal of Cataract & Refractive Surgery. 2019;45(3):343–350.30691922
41 Shenoy P, Goh EJH, Kashikar R, . Impact of prophylactic intracameral moxifloxacin on post-cataract surgery endophthalmitis: data from a tertiary eye care facility in rural India. International Ophthalmology. 2021;41(8):2729–2736.33821388
42 Shorstein NH, Liu L, Carolan JA, Herrinton L. Endophthalmitis Prophylaxis Failures in Patients Injected With Intracameral Antibiotic During Cataract Surgery. American Journal of Ophthalmology. 2021;227:166–172.33571472
43 Vieira IV, Boianovsky C, Saraiva TJ, Godoy RB, Lake J. Safety and efficacy of intracameral moxifloxacin injection for prophylaxis of endophthalmitis after phacoemulsification. Arquivos Brasileiros de Oftalmologia. 2017;80(3):165–167.28832735
44 Zhou AX, Messenger WB, Sargent S, Ambati BK. Safety of undiluted intracameral moxifloxacin without postoperative topical antibiotics in cataract surgery. International Ophthalmology. 2016;36(4):493–498.26577588
45 Cetinkaya S, Cetinkaya YF, Acir NO, Dadaci Z. Application of intracameral moxifloxacin to prevent endophthalmitis in cataract surgery. International Eye Science. 2015;15(10):1680–1683.
46 Lane SS, Osher RH, Masket S, Belani S. Evaluation of the safety of prophylactic intracameral moxifloxacin in cataract surgery. J Cataract Refract Surg. 2008;34(9):1451–1459.18721703
47 Matsuura K, Miyoshi T, Suto C, Akura J, Inoue Y. Efficacy and safety of prophylactic intracameral moxifloxacin injection in Japan. J Cataract Refract Surg. 2013;39(11):1702–1706.24054967
48 Matsuura K, Suto C, Inoue Y, Sasaki S, Odawara S, Gotou T. Safety of intracameral injection of moxifloxacin using total replacement technique (bag and chamber flushing). J Ocul Pharmacol Ther. 2014;30(9):771–776.25144127
49 Bhargava R, Kumar P, Sharma SK, Arora Y. Phacoemulsification Versus Manual Small Incision Cataract Surgery in Patients With Fuchs Heterochromic Iridocyclitis. The Asia-Pacific Journal of Ophthalmology. 2016;5(5):330–334.26939115
50 Types of Cataract Surgery. Wills Eye Hospital. https://www.willseye.org/centers-for-advanced-cataract-surgery/types-cataract-surgery/. Accessed April 5, 2022.
51 Ahee J. Safety and Efficacy of Intracameral Zimoxin for Prevention of Endophthalmitis After Cataract Surgery. NCT03244072 https://clinicaltrials.gov/ct2/show/NCT03244072?term=NCT03244072&draw=2&rank=1. Updated April 21, 2021. Accessed April 5, 2022.
52 Havnaer AG, Greenberg PB, Cockerham GC, Clark MA, Chomsky A. Cataract surgery practices in the United States veterans health administration. Journal of Cataract & Refractive Surgery. 2017;43(4):543–551.28532941

## Supplemental Materials

Download Supplemental Materials PDF

### APPENDIX A SEARCH STRATEGY

#### SYSTEMATIC REVIEWS

Search for current systematic reviews (limited to last 7 years); Date Searched: 01-31-22
A. Bibliographic Databases: | # | Search Statement | Results
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to January 28, 2022 | [underlined: 1] | exp Cataract Extraction/ OR Phacoemulsification/ OR ((cataract adj1 (surger* OR extraction)) OR capsulorhexis OR phacoemulsification$1).ti,ab. | 45041
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to January 28, 2022 | [underlined: 2] | Moxifloxacin/ OR (Avelox OR Moxeza OR Vigamox OR moxifloxacin).ti,ab. | 5574
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to January 28, 2022 | [underlined: 3] | 1 AND 2 | 201
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to January 28, 2022 | [underlined: 4] | [underlined: (systematic review.ti. or meta-analysis.pt. or meta-analysis.ti. or systematic literature review.ti. or this systematic review.tw. or pooling project.tw. or (systematic review.ti,ab. and review.pt.) or meta synthesis.ti. or meta-analy*.ti. or integrative review.tw. or integrative research review.tw. or rapid review.tw. or umbrella review.tw. or consensus development conference.pt. or practice guideline.pt. or drug class reviews.ti. or cochrane database syst rev.jn. or acp journal club.jn. or health technol assess.jn. or evid rep technol assess summ.jn. or jbi database system rev implement rep.jn. or (clinical guideline and management).tw. or ((evidence based.ti. or evidence-based medicine/ or best practice*.ti. or evidence synthesis.ti,ab.) and (((review.pt. or diseases category/ or behavior.mp.) and behavior mechanisms/) or therapeutics/ or evaluation studies.pt. or validation studies.pt. or guideline.pt. or pmcbook.mp.)) or (((systematic or systematically).tw. or critical.ti,ab. or study selection.tw. or ((predetermined or inclusion) and criteri*).tw. or exclusion criteri*.tw. or main outcome measures.tw. or standard of care.tw. or standards of care.tw.) and ((survey or surveys).ti,ab. or overview*.tw. or review.ti,ab. or reviews.ti,ab. or search*.tw. or handsearch.tw. or analysis.ti. or critique.ti,ab. or appraisal.tw. or (reduction.tw. and (risk/ or risk.tw.) and (death or recurrence).mp.)) and ((literature or articles or publications or publication or bibliography or bibliographies or published).ti,ab. or pooled data.tw. or unpublished.tw. or citation.tw. or citations.tw. or database.ti,ab. or internet.ti,ab. or textbooks.ti,ab. or references.tw. or scales.tw. or papers.tw. or datasets.tw. or trials.ti,ab. or meta-analy*.tw. or (clinical and studies).ti,ab. or treatment outcome/ or treatment outcome.tw. or pmcbook.mp.))) not (letter or newspaper article).pt.] | 498160
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to January 28, 2022 | [underlined: 5] | [underlined: 3 AND 4] | [underlined: 6]
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to January 28, 2022 | [underlined: 6] | [underlined: limit 5 to english language] | [underlined: 6]
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to January 26, 2022 | 1 | (Cataract Extraction OR Phacoemulsification).kw. OR ((cataract adj1 (surger* OR extraction)) OR capsulorhexis OR phacoemulsification$1).ti,ab. | 55
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to January 26, 2022 | 2 | Moxifloxacin.kw. OR (Avelox OR Moxeza OR Vigamox OR moxifloxacin).ti,ab. | 6
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to January 26, 2022 | 3 | 1 AND 2 | 0

Search for current systematic reviews (limited to last 7 years); Date Searched: 01-31-22
B. Non-bibliographic databases | [underlined: Evidence] | [underlined: Results]
AHRQ: evidence reports, technology assessments, U.S Preventative Services Task Force Evidence Synthesis | http://www.ahrq.gov/research/findings/evidence-based-reports/search.html; Search: moxifloxacin; cataract surgery | 0
CADTH | https://www.cadth.ca; Search: moxifloxacin; cataract surgery | 0
ECRI Institute | https://guidelines.ecri.org/; Search: moxifloxacin; cataract surgery | 0
HTA: Health Technology Assessments (UP TO 2016) | http://www.ohsu.edu/xd/education/library/; See CDSR search above | 0
NHS Evidence | http://www.evidence.nhs.uk/default.aspx; Search: moxifloxacin; cataract surgery; NIHR Alert: Antibiotics by injection into the eye can prevent severe infection following cataract surgery. 2017. NIHR Evidence.; https://evidence.nihr.ac.uk/alert/antibiotics-by-injection-into-the-eye-can-prevent-severe-infection-following-cataract-surgery/ | 1
EPPI-Centre | http://eppi.ioe.ac.uk/cms/Default.aspx?tabid=62; Use browser search function [CNTL + F] for keyword search; Search: moxifloxacin; cataract surgery | 0
NLM | http://www.ncbi.nlm.nih.gov/books; Search: moxifloxacin; cataract surgery | 0
VA Products - VATAP, PBM and HSR&D publications | A. http://www.hsrd.research.va.gov/research/default.cfm; B. http://www.research.va.gov/research_topics/; C. https://va.dimensions.ai/discover/publication; Search: moxifloxacin; cataract surgery | 0

#### PRIMARY STUDIES

Search for primary literature; Date searched: 02-04-22
MEDLINE [Ovid MEDLINE(R) ALL 1946 to February 03, 2022]
# | Search Statement | Results
[underlined: 1] | exp Cataract Extraction/ OR Phacoemulsification/ OR ((cataract adj1 (surger* OR extraction)) OR capsulorhexis OR phacoemulsification$1 OR (ophthalmologic surgical procedure) OR ophthalmic surger*).ti,ab. | 46325
[underlined: 2] | Moxifloxacin/ OR (Avelox OR Moxeza OR Vigamox OR moxifloxacin).ti,ab. | 5579
[underlined: 3] | 1 AND 2 | 205
4 | limit 3 to 2016 and English language | 114
CINAHL
# | Search Statement | Results
1 | (MH “Cataract Extraction+”) OR (MH “Phacoemulsification”) | 8548
2 | TI ( ((cataract N1 (surger* OR extraction)) OR capsulorhexis OR phacoemulsification$1 OR (ophthalmologic surgical procedure) OR ophthalmic surger*) ) OR AB ( ((cataract N1 (surger* OR extraction)) OR capsulorhexis OR phacoemulsification$1 OR (ophthalmologic surgical procedure) OR ophthalmic surger*) ) | 5558
3 | 1 OR 2 | 9933
4 | TI ( Avelox OR Moxeza OR Vigamox OR moxifloxacin ) OR AB ( Avelox OR Moxeza OR Vigamox OR moxifloxacin ) | 978
5 | 3 AND 4 | 58
6 | limit 5 to 2016 and English language | 37

### APPENDIX B EXCLUDED STUDIES

Exclude reasons: 1=Ineligible population, 2=Ineligible intervention, 3=Ineligible comparator, 4=Ineligible outcome, 5=Ineligible timing, 6=Ineligible study design, 7=Ineligible publication type, 8=Outdated or ineligible systematic review, 9=Non-English language, 10=Unable to locate.

Citation | Exclude Reason
Anijeet DR, Palimar P, Peckar CO. Intracameral vancomycin following cataract surgery: An eleven-year study. Clin Ophthalmol. 2010;4:321–326.20463800 20463800 | E2
Arbisser LB. Safety of intracameral moxifloxacin for prophylaxis of endophthalmitis after cataract surgery. J Cataract Refract Surg. 2008;34(7):1114–1120.18571078 | E4
Arshinoff SA, Modabber M. Dose and administration of intracameral moxifloxacin for prophylaxis of postoperative endophthalmitis. Journal of Cataract & Refractive Surgery. 2016;42(12):1730–1741.28007104 | E3
Arslan OS, Arici C, Unal M, Cicik E, Mangan MS, Atalay E. Safety of prophylactic intracameral moxifloxacin ophthalmic solution after cataract surgery in patients with penetrating keratoplasty. Int J Ophthalmol. 2014;7(5):795–799.25349795 | E3
Asencio MA, Huertas M, Carranza R, Tenias JM, Celis J, Gonzalez-del Valle F. Impact of changes in antibiotic prophylaxis on postoperative endophthalmitis in a Spanish hospital. Ophthalmic Epidemiol. 2014;21(1):45–50.24467562 | E2
Ashraf B, Elkhouly S, Nematalla EH, Mostafa A. Safety of Prophylactic Intracameral Moxifloxacin Injection after Uncomplicated Phacoemulsification Surgery. Egyptian Journal of Ophthalmology,(Mansoura Ophthalmic Center). 2022:46–54. | E4
Au CP, White AJ, Healey PR. Efficacy and cost-effectiveness of intracameral vancomycin in reducing postoperative endophthalmitis incidence in Australia. Clin Exp Ophthalmol. 2016;44(9):803–811.27311743 | E2
Barreau G, Mounier M, Marin B, Adenis JP, Robert PY. Intracameral cefuroxime injection at the end of cataract surgery to reduce the incidence of endophthalmitis: French study. J Cataract Refract Surg. 2012;38(8):1370–1375.22814043 | E2
Beselga D, Campos A, Castro M, . Postcataract surgery endophthalmitis after introduction of the ESCRS protocol: a 5-year study. Eur J Ophthalmol. 2014;24(4):516–519.24366770 | E2
Cavalcanti Lira RP, Lucena NP, Ferreira KS, Santos BM. Long-term safety of intracameral moxifloxacin after cataract surgery. Journal of Cataract & Refractive Surgery. 2017;43(1):139–140.28317668 | E4
Colleaux KM, Hamilton WK. Effect of prophylactic antibiotics and incision type on the incidence of endophthalmitis after cataract surgery. Can J Ophthalmol. 2000;35(7):373–378.11192445 | E2
Coskun M, Altintas AG, Anayol MA, Raza S, Celikbilek N, Simsek S. Evaluation of efficacy of topical povidone-iodine and different types of fluoroquinolones in the sterilization of bacterial flora on the conjunctiva. J Ocul Pharmacol Ther. 2011;27(6):589–592.21834670 | E2
Espiritu CR, Caparas VL, Bolinao JG. Safety of prophylactic intracameral moxifloxacin 0.5% ophthalmic solution in cataract surgery patients. J Cataract Refract Surg. 2007;33(1):63–68.17189795 | E3
Feijo ED. Intracameral moxifloxacin after cataract surgery: a prospective study. Response: Intracameral moxifloxacin after cataract surgery: a prospective study. Long-term safety of intracameral moxifloxacin after cataract surgery Intracameral antibiotics during cataract surgery: evidence and barriers. Arquivos Brasileiros de Oftalmologia. 2018;81(5):455–456.30208151 | E7
Ferreira BG, Cardoso da Silva I, Melega MV, . Macular and choroidal thickness after intracameral moxifloxacin for prevention of postcataract endophthalmitis. Journal of Cataract & Refractive Surgery. 2021;47(1):40–45.32818353 | E4
Group EES. Prophylaxis of postoperative endophthalmitis following cataract surgery: Results of the ESCRS multicenter study and identification of risk factors. Journal of Cataract & Refractive Surgery. 2007;33(6):978–988.17531690 | E2
Grzybowski A, Koerner JC, George MJ. Postoperative endophthalmitis after cataract surgery: a worldwide review of etiology, incidence and the most studied prophylaxis measures. Expert Review of Ophthalmology. 2019;14(4/5):247–257. | E7
Guttman Krader C. Clinical trial suggests safety of unpreserved levofloxacin: Intracameral injection of cefuroxime, moxil oxacin decrease risk of endophthalmitis. Ophthalmology Times. 2019;44(11):14–14. | E10
Halachmi-Eyal O, Lang Y, Keness Y, Miron D. Preoperative topical moxifloxacin 0.5% and povidone-iodine 5.0% versus povidone-iodine 5.0% alone to reduce bacterial colonization in the conjunctival sac. J Cataract Refract Surg. 2009;35(12):2109–2114.19969216 | E2
He L, Ta CN, Hu N, Sinnar S, Miño de Kaspar H. Prospective randomized comparison of 1-day and 3-day application of topical 0.5% moxifloxacin in eliminating preoperative conjunctival bacteria. J Ocul Pharmacol Ther. 2009;25(4):373–378.19492956 | E2
Inoue Y, Usui M, Ohashi Y, Shiota H, Yamazaki T. Preoperative disinfection of the conjunctival sac with antibiotics and iodine compounds: a prospective randomized multicenter study. Jpn J Ophthalmol. 2008;52(3):151–161.18661264 | E2
Jabbarvand M, Hashemian H, Khodaparast M, Jouhari M, Tabatabaei A, Rezaei S. Endophthalmitis Occurring after Cataract Surgery: Outcomes of More Than 480 000 Cataract Surgeries, Epidemiologic Features, and Risk Factors. Ophthalmology. 2016;123(2):295–301.26704882 | E7
Li A, Shao J, Gans R, Bena J, Goshe J. Postoperative Endophthalmitis Before and After Preferred Utilization of Prophylactic Intracameral Antibiotics for Phacoemulsification Cataract Surgeries at Cole Eye Institute. Eye & Contact Lens: Science & Clinical Practice. 2019;45(5):306–309. | E2
Li B, Miño de Kaspar H, Haritoglou C, . Comparison of 1-day versus 1-hour application of topical neomycin/polymyxin-B before cataract surgery. J Cataract Refract Surg. 2015;41(4):724–731.25840297 | E2
Linnehan R. Triamcinolone-moxifloxacin stabilizes macular thickness after cataract surgery in DR. Ocular Surgery News. 2020;38(19):18–18. | E2
Linnehan R. Optimal dose, concentration of moxifloxacin needed to prevent endophthalmitis. Ocular Surgery News. 2021;39(8):15–15. | E7
Lucena NP, Pereira IMS, Gaete MIL, Ferreira KSA, Melega MV, Lira RPC. Intracameral moxifloxacin after cataract surgery: a prospective study. Arquivos Brasileiros de Oftalmologia. 2018;81(2):92–94.29846429 | E3
Mamalis N. Reducing the risk of endophthalmitis. Journal of Cataract & Refractive Surgery. 2019;45(9):1217–1218.31470938 | E7
Miño de Kaspar H, Kreutzer TC, Aguirre-Romo I, . A prospective randomized study to determine the efficacy of preoperative topical levofloxacin in reducing conjunctival bacterial flora. Am J Ophthalmol. 2008;145(1):136–142.17996212 | E2
Mitchell W, Tom L, Durai I, . The Effectiveness of Intracameral Moxifloxacin Endophthalmitis Prophylaxis for Trabeculectomy. Ophthalmology Glaucoma. 2021;4(1):11–19.32738509 | E1
Moss JM, Nguyen D, Liu YI, . Comparison of one-day versus one-hour application of topical gatifloxacin in eliminating conjunctival bacterial flora. Ophthalmology. 2008;115(11):2013–2016.18708260 | E2
Myneni J, Desai SP, Jayamanne DG. Reduction in postoperative endophthalmitis with intracameral cefuroxime. J Hosp Infect. 2013;84(4):326–328.23834989 | E2
Patel SB, Reddy NK, He YG. Toxic Posterior Segment Syndrome after Dropless Cataract Surgery with Compounded Triamcinolone-Moxifloxacin. Retina. 2020;40(3):446–455.30689622 | E3
Rahman N, Murphy CC. Impact of intracameral cefuroxime on the incidence of postoperative endophthalmitis following cataract surgery in Ireland. Ir J Med Sci. 2015;184(2):395–398.24846749 | E2
Rathi V, Sharma S, Das T, Khanna R, Rathi VM, Khanna RC. Endophthalmitis Prophylaxis Study, Report 2: Intracameral antibiotic prophylaxis with or without postoperative topical antibiotic in cataract surgery. Indian Journal of Ophthalmology. 2020;68(11):2451–2455.33120637 | E2
Röck T, Bramkamp M, Bartz-Schmidt K, . Using intracameral cefuroxime reduces postoperative endophthalmitis rate: 5 years experience at the University Eye Hospital Tübingen. Klinische Monatsblatter fur Augenheilkunde. 2014;231(10):1023–1028.25333241 | E9
Rudnisky CJ, Wan D, Weis E. Antibiotic choice for the prophylaxis of post-cataract extraction endophthalmitis. Ophthalmology. 2014;121(4):835–841.24326107 | E2
Rush SW, Vu D, Rush RB. The Safety and Efficacy of Routine Administration of Intracameral Vancomycin during Cataract Surgery. J Ophthalmol. 2015;2015:813697.26617996 | E2
Sharma S, Sahu SK, Dhillon V, Das S, Rath S. Reevaluating intracameral cefuroxime as a prophylaxis against endophthalmitis after cataract surgery in India. J Cataract Refract Surg. 2015;41(2):393–399.25535109 | E2
Shorstein NH, Winthrop KL, Herrinton LJ. Decreased postoperative endophthalmitis rate after institution of intracameral antibiotics in a Northern California eye department. J Cataract Refract Surg. 2013;39(1):8–14.23036356 | E2
Ta CN, Chan I, Dhatt HS, . Prospective comparison of topical moxifloxacin in eliminating conjunctival bacterial flora following a one-day or one-hour application. J Ocul Pharmacol Ther. 2008;24(4):427–431.18665815 | E2
Ta CN, Egbert PR, Singh K, Shriver EM, Blumenkranz MS, Miño De Kaspar H. Prospective randomized comparison of 3-day versus 1-hour preoperative ofloxacin prophylaxis for cataract surgery. Ophthalmology. 2002;109(11):2036–2040; discussion 2040-2031.12414411 | E2
Ta CN, Sinnar S, He L, Myung D, Miño De Kaspar H. Prospective randomized comparison of 1-day versus 3-day application of topical levofloxacin in eliminating conjunctival flora. Eur J Ophthalmol. 2007;17(5):689–695.17932841 | E2
Tan CS, Wong HK, Yang FP. Epidemiology of postoperative endophthalmitis in an Asian population: 11-year incidence and effect of intracameral antibiotic agents. J Cataract Refract Surg. 2012;38(3):425–430.22245169 | E2
Vidyadevi M, Anuradha A, Rashmi G, Shilpa R, Nishath S. Safety of Fixed drug Combination in Post -Operative Cataract Patients, at Tertiary Care Centre - In South India. Nepalese Journal of Ophthalmology : A Biannual Peer-reviewed Academic Journal of the Nepal Ophthalmic Society : NEPJOPH. 2017;9(18):24–29.29022951 | E2
Yu-Wai-Man P, Morgan SJ, Hildreth AJ, Steel DH, Allen D. Efficacy of intracameral and subconjunctival cefuroxime in preventing endophthalmitis after cataract surgery. Journal of Cataract & Refractive Surgery. 2008;34(3):447–451.18299070 | E2

### APPENDIX C EVIDENCE TABLES

#### CHARACTERISTICS OF INCLUDED PRIMARY STUDIES

#### OUTCOME DATA OF INCLUDED PRIMARY STUDIES

Endophthalmitis

Other Adverse Events

#### QUALITY ASSESSMENT OF INCLUDED PRIMARY STUDIES

Randomized Controlled Trials

Observational Studies

#### STRENGTH OF EVIDENCE FOR INCLUDED STUDIES

Strength of Evidence for Endophthalmitis

### APPENDIX D RESEARCH IN PROGRESS

Status | Study Title | Study Design | Information Resources
Completed; (Not published) | Intracameral Moxifloxacin for Prevention of Post cataract Endophthalmitis | Single group assignment | NCT02595359
Completed; (Not published) | Postoperative Safety Outcomes of Intraoperative Intracameral Preservative-Free Moxifloxacin Versus Levofloxacin | RCT | NCT04403334
Not yet recruiting | Safety and Efficacy of Intracameral Zimoxin for Prevention of Endophthalmitis After Cataract Surgery | RCT | NCT03244072

Abbreviations. RCT=Randomized controlled trials.

### APPENDIX E PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | None
2 | 2 | Yes | None
3 | 3 | Yes | None
4 | 4 | Yes | None
Is there any indication of bias in our synthesis of the evidence?
5 | 1 | No | None
6 | 2 | No | None
7 | 3 | No | None
8 | 4 | Yes - The authors are biased in favor of moxifloxacin use, perhaps due to standard of care. | We have addressed the specific comments below.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
9 | 1 | No | None
10 | 2 | No | None
11 | 3 | Yes - Included in my comments below | Addressed in comments below.
12 | 4 | Yes - - Mamalis N. Reducing the risk of endophthalmitis. J Cataract Refract Surg 2019;45 (9):1217–1218.31470938; - Novack GD, Caspar JJ. Peri-Operative Intracameral Antibiotics: The Perfect Storm? J Ocul Pharmacol Ther 2020;36 (9):668–671.32580612 | We identified both of these studies in our search, and they were not formally included as they are editorials/ commentaries of a study we included (Haripriya). We have added Novack 2020 to the background and discussion sections.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
13 | 1 | Page 4 line 38: Intracameral antibiotics are given at the end of the case after IOL insertion and viscoelastic removal not “immediately after Cataract removal” | This has been revised to clarify when intracameral antibiotics are given.
14 | 1 | Page 4 Line 53: topical or “injectable” - I believe cefuroxime and Vancomycin are injectables not topicals | We have added “injectable” after topical here.
15 | 1 | Page 6 line 25: This endophthalmitis rate seems high…is there a range reported and is this only Post-op endophthalmitis | Thank you, this number was incorrectly reported, and we have revised it to a range of 0.08% to 0.14%.
16 | 1 | Page 6 line 48: Injected at the end of the case- not “immediately after cataract removal” | This has been revised to clarify when intracameral antibiotics are given.
17 | 1 | Page 6 line55: Can we confirm there was an arm of no antibiotics in this study. I believe the fine print * under the table depicting the arms it states all arms received topical antibiotics. | Thank you for pointing this out. We have removed the “no antibiotic use” as the table notes do state that all patients received postoperative topical antibiotics.
18 | 1 | Page 19 line 4 topical or “injectable” | We have added “injectable” after topical here.
19 | 1 | Page 19 line 34 Should this state Intracameral moxifloxacin “alone” versus topical- Just to clarify | Yes, thank you, this is a good clarification. We have added “alone” after intracameral moxifloxacin.
20 | 2 | Excellent review of relevant literature, including recent sources. | Thank you.
21 | 3 | This is an extremely well written manuscript that is organized and supports its final conclusion. Despite the comprehensive nature of the review, there are a few omissions: | Thank you, individual comments addressed below.
22 | 3 | Background:; The authors did not include that the current community standard is to concurrently prescribe two medications. A topical antibiotic, most commonly a fluroquinolone, and a topical steroid drop. There is strong evidence within both the ophthalmic and general medical literature that the addition of a second medication dramatically reduces the adherence/compliance with both medications compared to a single prescribed medication. | Thank you. We have added that steroid drops are also often prescribed with topical antibiotics, and this can also hinder patient adherence.
23 | 3 | Although the authors did not include the reported cases of TASS due to administering a topically preparation into the eye, they did not include the reported cases of TASS that occurred from compounded formulations. | Thank you, this is an important point. We have added to the background and discussion the risk of TASS with compounded moxifloxacin.
24 | 3 | Methods:; The methodology utilized is standard for high quality reviews and meta-analyses | Thank you.
25 | 3 | Results:; In the adverse effects of moxifloxacin use, there is a prospective randomized controlled trial comparing two intracameral doses of moxifloxacin on corneal endothelial cell counts finding no difference in safety. However, it is a recent publication in January of 2022 which may have been after this document was prepared.; The ESCRS PRCT has some methodologic flaws preventing FDA acceptance of this data for approval – a deeper discussion could have been described. | Thank you for letting us know of this study. We have found Ashraf 2008 “Safety of Prophylactic Intracameral Moxifloxacin Injection after Uncomplicated Phacoemulsification Surgery” and have reviewed it. As the study does not report endophthalmitis rates or moxifloxacin related adverse events, we have formally excluded it.
26 | 3 | Conclusions:; The current data is strongly suggestive of the superior efficacy of intracameral moxifloxacin for the prevention of endophthalmitis following cataract surgery. However, only a level 1 PRCT can definitively determine therapeutic superiority and safety. | We agree and suggest further RCTs in our future research section.
27 | 3 | This is an excellent review and the minor omissions of information do not materially change the conclusion of the authors. | Thank you.
28 | 4 | The authors prepared a “Cochrane review” like document on the issue of use of intracameral moxifloxacin for prevention of endophthalmitis after cataract surgery. At first read, it seems like a very straightforward manuscript, supporting this use. However, on deeper read, several items are not fully described. Other issues, brought up in some recent papers, are seemingly not completely addressed. Thus, I suggest that a reader of this document may come to an inappropriate conclusion about the safety, efficacy and benefit-risk of moxifloxacin by this route. | Thank you for your comments, we have addressed them individually below.
29 | 4 | In the executive summary, the authors state: “..Intracameral antibiotics are effective at preventing endophthalmitis.” This is arguably not true. Other than a few select studies, there are no randomized trials with concurrent negative controls (e.g., placebo). Without an approved positive control (and there is none in the U.S. – topical or intracameral), a positivecontrolled study is not conclusive. | We have revised discussion of existing research to more accurately describe evidence on intracameral antibiotics in light of methodological limitations of available studies.
30 | 4 | The authors further state “.there are currently no antibiotics that are approved by the US Food and Drug Administration for intraocular use”. The reason for this lack of approved products is simple – there are no publicly submitted applications, presumably due to the lack of the required two concurrent negative controlled trials. | We agree and discuss in our future research section that further RCTs in the US, including a current ongoing placebo controlled RCT, are needed to impact FDA approval.
31 | 4 | They state “US surgeons must use repackaged and diluted topical solutions off-label. Increased risk, liability, and logistical challenges of using antibiotics off-label has led to less intracameral antibiotic use in the US compared to other countries where commercial intracameral formulations are available”. This is exactly the point – but one seemingly not discussed further in the conclusions. These risks must be considered by the surgeon in opting for off-label, compounded intracameral moxifloxacin. Do the authors propose a solution for the VA system – for example, a standard formulation by the pharmacies? | We have added further discussion of potential increased risk from using off-label compounded moxifloxacin in the US to the discussion of VHA considerations. In the section on considerations for VHA, we discuss the need for either an FDA approved intracameral formulation or standardized VHA pharmacy preparation in order to standardize use within the VHA.
32 | 4 | The authors state that there is new evidence beyond the cited review papers (Lane 2008; Matsurra 2014 and Melaga 2019). Is it explicitly stated what this new evidence is? Perhaps it is Haripriya 2019? That paper is large – but unfortunately, sequential and not randomized. I suggest the authors asterisk the “new” studies in Table 1. | We have added a footnote to Table 1 identifying the studies not included in previous reviews, and also cite these studies in the discussion section.
33 | 4 | The authors blur studies with antibiotics other than moxifloxacin. Just because something was found with one intracameral antibiotic does not mean moxifloxacin is safe and effective. | Studies included in our synthesis examine intracameral moxifloxacin and we did not include studies of other intracameral antibiotics. Although several of our included studies did compare intracameral antibiotics to another intracameral antibiotic (cefuroxime), we separated this out in a comparative effectiveness analysis.
34 | 4 | The authors state: “Due to concerns around antibiotic resistance and potential adverse events from use of cefuroxime and vancomycin, moxifloxacin has more recently been investigated.” That may be true, however I suggest that the real reason is that marketed topical moxifloxacin is “self-preserved” – i.e., free of a preservative, which would be inappropriate to use by intracameral route. | We agree that the availability of moxifloxacin without preservatives has likely influenced more recent use. We have added a statement about the availability of moxifloxacin without preservatives.
35 | 4 | Further, it is essential that the correct formulation of moxifloxacin is used by the pharmacy for preparing the intracameral product. That is, as I understand, Vigamox® rather than Moxeza®. | We agree. We discuss the brands and dosages used in the studies included in the report in the discussion section and have added a statement about considering potential adverse effects with other brands.
36 | 4 | Of the many papers excellently reviewed, there are seemingly only two negative controlled trials.; -Melage 2019. I suggest that the authors state the findings of this study in the body of the manuscript: “The incidence of endophthalmitis within 6 weeks of follow-up was 1 (0.05%) of 1818 eyes in the moxifloxacin group and 7 (0.38%) of 1822 eyes in the control group (P Z .035).; -Lane 2008. This study was not designed nor powered to evaluate endophthalmitis rate. | We have added the Melaga 2019 findings to the narrative results. We agree that Lane 2008 was not designed to evaluate endophthalmitis and it is not included in our synthesis of endophthalmitis but was included for its assessment of adverse events.
37 | 4 | The authors may consider reiterating the risk of endophthalmitis (<< 1% without antibiotics). This may help interpret Figure 2. While large Odds Ratios are found – the number needed to treat is very high. | We have added the low rate of endophthalmitis to the discussion section to contextualize the odds ratio.
38 | 4 | The authors may consider the antithetical status – while intracameral moxifloxacin is not approved, it may nonetheless be the standard of care, leading to medico-legal issues. | This is a good point and we have added a statement to the future research section to note this.
39 | 4 | The authors may consider these two commentaries:; - Mamalis N. Reducing the risk of endophthalmitis. J Cataract Refract Surg 2019;45 (9):1217–1218.31470938; - Novack GD, Caspar JJ. Peri-Operative Intracameral Antibiotics: The Perfect Storm? J Ocul Pharmacol Ther 2020;36 (9):668–671.32580612 | Thank you for these suggestions. We have added Novack 2020 to the background and discussion sections.

### REFERENCES

1 Arshinoff SA, Bastianelli PA. Incidence of postoperative endophthalmitis after immediate sequential bilateral cataract surgery. J Cataract Refract Surg. 2011;37(12):2105–2114.22108106
2 Bhatta S, Pant N, Poudel M. Postoperative endophthalmitis with and without intracameral moxifloxacin prophylaxis in a high volume surgery setting. BMJ Open Ophthalmology. 2021;6(1):e000609.
3 Cetinkaya S, Cetinkaya YF, Acir NO, Dadaci Z. Application of intracameral moxifloxacin to prevent endophthalmitis in cataract surgery. International Eye Science. 2015;15(10):1680–1683.
4 Dave V, Singh V, Reddy J, Sharma S, Joseph J, Das T. Clinical features and microbiology of post-cataract surgery endophthalmitis with and without intracameral moxifloxacin prophylaxis: Endophthalmitis prophylaxis study report 3. Indian Journal of Ophthalmology. 2022;70(1):158–163.34937229
5 Ekinci Koktekir B, Aslan BS. Safety of prophylactic intracameral moxifloxacin use in cataract surgery. J Ocul Pharmacol Ther. 2012;28(3):278–282.22304496
6 Friling E, Lundström M, Stenevi U, Montan P. Six-year incidence of endophthalmitis after cataract surgery: Swedish national study. J Cataract Refract Surg. 2013;39(1):15–21.23245359
7 Galvis V, Tello A, Sánchez MA, Camacho PA. Cohort study of intracameral moxifloxacin in postoperative endophthalmitis prophylaxis. Ophthalmol Eye Dis. 2014;6:1–4.24526838
8 Haripriya A, Chang DF, Namburar S, Smita A, Ravindran RD. Efficacy of Intracameral Moxifloxacin Endophthalmitis Prophylaxis at Aravind Eye Hospital. Ophthalmology. 2016;123(2):302–308.26522705
9 Haripriya A, Chang DF, Ravindran RD. Endophthalmitis Reduction with Intracameral Moxifloxacin Prophylaxis: Analysis of 600 000 Surgeries. Ophthalmology. 2017;124(6):768–775.28214101
10 Haripriya A, Chang DF, Ravindran RD. Endophthalmitis reduction with intracameral moxifloxacin in eyes with and without surgical complications: Results from 2 million consecutive cataract surgeries. Journal of Cataract & Refractive Surgery. 2019;45(9):1226–1233.31371152
11 Herrinton LJ, Shorstein NH, Paschal JF, . Comparative Effectiveness of Antibiotic Prophylaxis in Cataract Surgery. Ophthalmology. 2016;123(2):287–294.26459998
12 Lane SS, Osher RH, Masket S, Belani S. Evaluation of the safety of prophylactic intracameral moxifloxacin in cataract surgery. J Cataract Refract Surg. 2008;34(9):1451–1459.18721703
13 Matsuura K, Miyoshi T, Suto C, Akura J, Inoue Y. Efficacy and safety of prophylactic intracameral moxifloxacin injection in Japan. J Cataract Refract Surg. 2013;39(11):1702–1706.24054967
14 Matsuura K, Suto C, Inoue Y, Sasaki S, Odawara S, Gotou T. Safety of intracameral injection of moxifloxacin using total replacement technique (bag and chamber flushing). J Ocul Pharmacol Ther. 2014;30(9):771–776.25144127
15 Melega MV, Alves M, Cavalcanti Lira RP, . Safety and efficacy of intracameral moxifloxacin for prevention of post-cataract endophthalmitis: Randomized controlled clinical trial. Journal of Cataract & Refractive Surgery. 2019;45(3):343–350.30691922
16 Porwal A, Patel A, Mathew B, . Incidence of postoperative endophthalmitis with and without use of intracameral moxifloxacin. In. Vol 68: Wolters Kluwer India Pvt Ltd; 2021:1353–1354.
17 Rathi V, Sharma S, Das T, Khanna R, Rathi VM, Khanna RC. Endophthalmitis prophylaxis study. Report 1: Intracameral cefuroxime and moxifloxacin prophylaxis for the prevention of postcataract endophthalmitis in rural India. Indian Journal of Ophthalmology. 2020;68(5):819–824.32317453
18 Shenoy P, Goh EJH, Kashikar R, . Impact of prophylactic intracameral moxifloxacin on post-cataract surgery endophthalmitis: data from a tertiary eye care facility in rural India. International Ophthalmology. 2021;41(8):2729–2736.33821388
19 Shorstein NH, Liu L, Carolan JA, Herrinton L. Endophthalmitis Prophylaxis Failures in Patients Injected With Intracameral Antibiotic During Cataract Surgery. American Journal of Ophthalmology. 2021;227:166–172.33571472
20 Vieira IV, Boianovsky C, Saraiva TJ, Godoy RB, Lake J. Safety and efficacy of intracameral moxifloxacin injection for prophylaxis of endophthalmitis after phacoemulsification. Arquivos Brasileiros de Oftalmologia. 2017;80(3):165–167.28832735
21 Zhou AX, Messenger WB, Sargent S, Ambati BK. Safety of undiluted intracameral moxifloxacin without postoperative topical antibiotics in cataract surgery. International Ophthalmology. 2016;36(4):493–498.26577588