# Evidence Brief: Impact of Mental Health Conditions on Peri-implantitis and Dental Implant Failure

## PREFACE

The VA Evidence Synthesis Program (ESP) was established in 2007 to provide timely and accurate syntheses of targeted health care topics of importance to clinicians, managers, and policymakers as they work to improve the health and health care of Veterans. These reports help:

- Develop clinical policies informed by evidence;
- Implement effective services to improve patient outcomes and to support VA clinical practice guidelines and performance measures; and
- Set the direction for future research to address gaps in clinical knowledge.

The program comprises four ESP Centers across the US and a Coordinating Center located in Portland, Oregon. Center Directors are VA clinicians and recognized leaders in the field of evidence synthesis with close ties to the AHRQ Evidence-based Practice Center Program. The Coordinating Center was created to manage program operations, ensure methodological consistency and quality of products, interface with stakeholders, and address urgent evidence needs. To ensure responsiveness to the needs of decision-makers, the program is governed by a Steering Committee composed of health system leadership and researchers. The program solicits nominations for review topics several times a year via the program website (https://www.hsrd.research.va.gov/publications/esp/TopicNomination.cfm).

The present report was developed in response to a request from the VHA Office of Dentistry, Oral Health Quality Group. The scope was further developed with input from Operational Partners (below) and the ESP Coordinating Center review team.

## ACKNOWLEDGMENTS

The authors are grateful to Kathryn Vela, MLIS for literature searching, Payten Sonnen for editorial and citation management support, and the following individuals for their contributions to this project:

### Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Gretchen Gibson, DDS, MPH
  Director
  Oral Health Quality Group, VHA Office of Dentistry

### Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix D in Supplemental Materials for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.

## EXECUTIVE SUMMARY

#### Background

The Evidence Synthesis Program Coordinating Center is responding to a request from the VHA Office of Dentistry, Oral Health Quality Group, for an Evidence Brief on the impact of mental health conditions on development of periimplantitis and dental implant failure. Findings from this Evidence Brief will be used to inform development and use of an implant risk assessment tool.

#### Methods

To identify studies, we searched MEDLINE, Cochrane Database of Systematic Reviews, CINAHL, PsycINFO, and other sources up to March 2022. We used prespecified criteria for study selection, data abstraction, and rating internal validity and strength of the evidence. See the Methods section and our PROSPERO protocol for full details of our methodology.

Key Findings

- Antidepressant use at the time of implant placement likely increases risk of implant failure based on moderate-strength evidence from 9 studies (N = 25,364 implants).
- Evidence from only the most rigorous available studies indicates that antidepressant use at the time of implant placement is associated with an approximately 20% increase in risk of early implant failure.
- Available evidence is insufficient to draw conclusions about the effect of mental health conditions on risk of implant failure, and no studies included peri-implantitis as an outcome of interest.
- Veteran implant candidates may benefit from approaches to screen for known and likely risk factors for implant failure, and from research on the effectiveness and feasibility of tailored periimplant maintenance programs.

Dental implants are an increasingly common intervention to address missing or damaged teeth, particularly among older adults and individuals without sufficient natural teeth roots to support dentures or fixed dental prosthesis. Implants are surgically placed in the bone, and over several months heal into the bone in a process known as osseointegration. Complications can occur during or after osseointegration and may ultimately result in loss of the implant.

Because placement requires incisions to the gums and extended periods of healing in a bacteria-rich environment, soft and hard tissues surrounding the implant site may become infected and inflamed. In advanced disease, known as peri-implantitis, chronic inflammation of the tissues around the implant results in loss of bone that can lead to implant failure. In addition to bacterial infection, inflammation, and bone loss at the implant site, other factors associated with increased risk of implant failure include prior gum disease (periodontitis), mechanical overloading of the implant (eg, bruxism, hyperocclusion), diabetes and hyperglycemia, and tobacco smoking.

Research in recent decades has also suggested a link between dental implant failure and use of medications commonly prescribed to treat depression, especially selective serotonin reuptake inhibitors (SSRIs). Additionally, depression or other mental health conditions may compromise immune function and lead to poorer dietary and oral hygiene practices. Conceivably, these systematic and behavioral changes could lead to oral inflammation and infections that, in turn, increase an implant recipient’s risk of peri-implantitis and implant failure. The present review aimed to synthesize evidence from studies examining the role of mental health conditions and SSRI use in peri-implantitis and dental implant failure risk.

Available evidence on the association between antidepressant use and implant failure risk is moderate strength and relies on 9 observational studies of varying size and rigor. Across these studies (N = 25,364 implants), approximately 1 in every 26 implants failed; about 1 in 9 implants failed among implant recipients on antidepressant medications, in contrast to 1 in every 34 among recipients not using antidepressants. When study results are pooled, antidepressant users experience significantly greater risk of implant failure than non-users (RR_Mean_ = 1.60, 95% confidence interval [1.21, 2.13]). The degree to which implant failure risk is increased varies across studies, but findings from the most rigorous studies indicate that antidepressant use at the time of implant placement is associated with an approximately 20% increase in risk of early implant failure.

A small number of studies investigated whether the presence of mental health conditions increases implant failure risk; although studies reported associations between depression or anxiety and implant failure, evidence from these studies is insufficient to make conclusions. Moreover, the mechanism by which mental health conditions influence implant failure risk remains unclear. No studies examined the impact of antidepressant use or mental health conditions on peri-implantitis risk.

Research is needed that would clarify relationships between mental health conditions, behavioral responses, and implant outcomes across a wide range of mental health conditions. In the nearer term, Veterans may benefit from research on, and implementation of, screening methods that would facilitate earlier detection of known and likely implant failure risk factors in implant candidates, as well as osseointegration issues in implant recipients. A screening tool for peri-implant disease risk factors has been recently published, and although this tool lacks an antidepressant use or mental health condition domain, one could potentially be added and evaluated within VA clinical settings. Additionally, evidence on tailored peri-implant maintenance therapy programs suggests that they may be helpful in limiting the impacts of implant failure risk factors regardless of their etiology, and as a result, these programs may constitute a promising innovation to be investigated for broad implementation in the VA.

In summary, moderate-strength evidence indicates that antidepressant use is likely associated with elevated risk of implant failure. Available studies provide suggestive evidence that implants may be at greater risk of failing before abutment placement, which is consistent with the purported mechanism by which antidepressants influence the osseointegration process and the likelihood of implant failure. Although antidepressant use alone may increase the risk of implant failure, many failures could be the result of a complex array of risk factors. Consequently, Veterans may benefit from approaches to better detect risk factors for implant failure prior to implant placement, as well as from future research on the effectiveness and feasibility of tailored peri-implant maintenance programs that could enable prevention and earlier detection and treatment of oral health-related risk factors for implant failure.

## INTRODUCTION

### PURPOSE

The Evidence Synthesis Program (ESP) Coordinating Center is responding to a request from the VHA Office of Dentistry, Oral Health Quality Group, for an Evidence Brief on the impact of mental health conditions on development of peri-implantitis and dental implant failure. Findings from this Evidence Brief will be used to inform development and use of an assessment tool to assess the aggregate risk of complications in VA patients requiring dental implants.

### BACKGROUND

Dental implants are an increasingly common intervention to address missing or damaged teeth, particularly among older adults and individuals without sufficient natural teeth roots to support dentures or fixed dental prosthesis.^1–3^ Implants are surgically placed in the bone, and over several months heal into the bone in a process known as osseointegration.^1,4,5^ At the time the implant is placed or after osseointegration, an abutment that extends beyond the gumline is connected to the implant to serve as the attachment point for one or more prosthetic teeth.^1,6^ Later placement of the abutment may be preferred by patients because the abutment is visible for a shorter period,^1^ but doing so requires a second gum incision^1,6^ that may increase complication risk. The prosthetic tooth, multiple bridged teeth, or a denture are loaded onto the abutment immediately, after a brief healing period (eg, 1–8 weeks), or after healing is completed.^7^ Single or bridged teeth are often fixed to the abutment and are cleaned alongside the patient’s natural teeth.^1^

Complications can occur after implant placement and may ultimately result in loss of the implant.^1,8^ Because placement requires incisions to the gums and extended periods of healing in a bacteria-rich environment, soft and hard tissues surrounding the implant site may become infected and inflamed.^5,9^ In advanced disease, known as peri-implantitis, chronic inflammation of the tissues around the implant results in loss of bone.^9^ Even minor bone loss associated with periimplantitis can lead to osseointegration failure and loss of newly placed implants.^8^ Implants may also fail after the initial healing process; in these cases, bone loss continues to the point of implant loss.^8^ In addition to bacterial infection and inflammation leading to bone loss at the implant site, other factors associated with increased risk of implant failure include prior gum disease (periodontitis), mechanical overloading of the implant (eg, bruxism), diabetes and hyperglycemia, and tobacco smoking.^1,10,11^

Research in recent decades has also suggested a link between dental implant failure and use of medications commonly prescribed to treat depression, especially selective serotonin reuptake inhibitors (SSRIs).^2,12,13^ It is known that SSRIs and other classes of antidepressant medications influence bone metabolism, potentially slowing implant osseointegration and elevating risk of implant failure.^2,12^ Additionally, depression or other mental health conditions may compromise immune function and lead to poorer dietary and oral hygiene practices.^14–16^ Conceivably, these systematic and behavioral changes could lead to oral inflammation and infections that, in turn, increase an implant recipient’s risk of peri-implantitis and implant failure. The present review aimed to synthesize evidence from studies examining the role of mental health conditions and SSRI use in peri-implantitis and dental implant failure risk.

## METHODS

### PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42022318701).

### KEY QUESTIONS

The following key questions (KQs) were the focus of this review:

KQ1 Among adults receiving dental implants, does presence and/or treatment of 1 or more comorbid mental health conditions (eg, posttraumatic stress disorder [PTSD], bipolar disorder, schizophrenia, depression, anxiety) increase risk of peri-implantitis or dental implant failure/loss?

### ELIGIBILITY CRITERIA

The ESP included studies that met the following criteria:

Population | Adults receiving 1 or more dental implants
Intervention | Placement of 1 or more dental implants in patients with a comorbid mental health condition (eg, PTSD, bipolar disorder, schizophrenia, depression, anxiety)
Comparator | Placement of 1 or more dental implants in patients without a comorbid mental health condition
Outcomes | - Diagnosis of peri-implantitis within 5 years of implant placement; - Failure/loss of dental implants within 5 years of implant placement
Timing | Any
Setting | Any
Study Design | Any, but we may prioritize articles using a best-evidence approach to accommodate Evidence Brief timeline

### DATA SOURCES AND SEARCHES

To identify articles relevant to the key questions, a research librarian searched Ovid MEDLINE, CINAHL, and PsycINFO, as well as AHRQ, Cochrane Database of Systematic Reviews, and HSR&D through March 2022 using terms for dental implant failure, peri-implantitis, mental health conditions, and SSRIs (see Appendix A in Supplemental Materials for complete search strategies). Additional citations were identified from hand-searching reference lists. We limited the search to published and indexed articles involving human subjects available in the English language. Study selection was based on the eligibility criteria described above. Titles, abstracts, and full-text articles were reviewed by 1 investigator and checked by another. All disagreements were resolved by consensus or discussion with a third reviewer.

### DATA ABSTRACTION AND ASSESSMENT

Effect information and population, intervention, and comparator characteristics were abstracted from all included studies. The internal validity (risk of bias) of each included study was rated using the Quality In Prognostic Studies (QUIPS)^17^ tool. The QUIPS tool includes 6 domains: study participation, study attrition, prognostic factor measurement, outcome measurement, study confounding, and statistical analysis and reporting. Domains are rated as low, moderate, or high risk of bias. As all our included studies obtained data via record review, we did not rate studies on the study attrition domain. Instead, missing data concerns were captured in other domains. Any study which was rated high in 2 or more domains was considered high overall risk of bias. Any study which was rated low risk of bias in all 6 domains was considered low overall risk of bias. Studies which did not meet either of those conditions were considered moderate overall risk of bias. All data abstraction and internal validity ratings were first completed by 1 reviewer and then checked by another; disagreements were resolved by consensus or discussion with a third reviewer.

We graded the strength of available evidence using an approach based on the AHRQ Methods Guide for Comparative Effectiveness Reviews,^18^ which provides a rating of confidence in reported findings based on study methodology (design, quality, and risk of bias), consistency (whether effects are in the same direction and have a consistent magnitude), and directness (whether assessed outcomes are clinically important to patients and providers). When information on precision of findings (eg, confidence intervals) is available, certainty of evidence is also evaluated. We used the following general algorithm: high strength evidence consisted of multiple, large studies with low risk of bias, consistent and precise findings, and clinically relevant outcomes; moderate strength evidence consisted of multiple studies with low to moderate risk of bias, consistent and precise findings, and clinically relevant outcomes; low strength evidence consisted of a single study, or multiple small studies, with moderate to high risk of bias, inconsistent or imprecise findings, and/or outcomes with limited clinical relevance; and insufficient evidence consisted of a single study with moderate or high risk of bias, or no available studies.

### SYNTHESIS

Few studies investigating the association of mental health conditions with dental implant failure were identified, and these studies were synthesized narratively. For studies of the association between antidepressant/SSRI use and implant failure, we synthesized available outcome data using random-effects meta-analyses. Studies included in meta-analyses reported outcomes as counts, proportions, or ratios, generally at the implant unit of analysis (1 study^13^ reported results at the person level, and while we included these findings in analyses, it is possible that results of this study underestimate the relation of antidepressant use with implant failure). When studies reported counts or proportions but did not provide an adjusted ratio, risk ratios (RRs) were calculated directly from cell counts (no cell contained zero events). Reported adjusted odds ratios were converted to RRs using the square-root transformation.^19^ Two studies^20,21^ included in meta-analyses reported adjusted hazard ratios (HRs), and because implant failure was rare in these studies (occurring in approximately 10% of the intervention group), we considered these HRs to be approximately equivalent to RRs.

For meta-analyses presented below, mean RRs less than 1 indicate benefits (ie, reduced risk) of implant failure among participants using antidepressants/SSRIs compared to those not using antidepressants/SSRIs, and RRs greater than 1 indicate increased failure risk compared to participants not using antidepressants/SSRIs. Precision of study-level ratios and mean RRs is reported using cluster-robust (sandwich) 95% confidence intervals (CIs). CIs were used to evaluate statistical significance of mean RRs at a significance level of .05. Heterogeneity in true study effects was estimated using restricted maximum-likelihood estimation and is presented as 95% prediction intervals (PIs).^22,23^ A PI encompassing values that substantively differ in direction and/or magnitude from the mean RRs indicates the presence of considerable heterogeneity. The Knapp-Hartung adjustment was used to account for imprecision in estimating the amount of heterogeneity.^24^ Meta-analyses were carried out using the metafor^25^ package for R (R Foundation for Statistical Computing, Vienna, Austria).

## RESULTS

### LITERATURE FLOW

The literature flow diagram (Figure 1) summarizes the results of the study selection process (full list of excluded studies available in Appendix B in Supplemental Materials).

Figure 1 Literature Flowchart

Notes. *Two systematic reviews^2,12^ met eligibility criteria but were excluded because all primary studies in those reviews were included in the present review.

Abbreviations. CDSR=Cochrane Database of Systematic Reviews; CINAHL=Cumulative Index to Nursing and Allied Health Literature; SR=systematic review.

### LITERATURE OVERVIEW

Our search identified 704 potentially relevant articles. Of these, 12 observational studies of retrospective^4,13,20,21,26^–^32^ or prospective^33^ cohorts met eligibility criteria and were included in the present review (see Table 1 for key study characteristics and Appendix C in the Supplemental Materials for additional study details). All included studies used clinical record data. The median sample size of studies was 561 participants (range: 54–5,456) or 1,376 implants (range: 224–10,096). Studies were conducted in the US or Canada (N = 5),^13,20,21,27,31^ Sweden (N = 3),^28–30^ Belgium (N = 2),^26,33^ India (N = 1),^32^ or Turkey (N = 1).^4^

Nine studies^4,13,20,21,26,28,29,32,33^ examined the occurrence of implant failures among patients prescribed antidepressants compared with patients not prescribed antidepressants (studies varied in whether they limited eligible antidepressants to SSRIs). Three additional studies compared implant failures among patients with and without mental health conditions (depression,^31^ depression or anxiety,^27^ or provider judgment of “psychological illness” as cause of failure^30^). The majority of studies counted implants that failed at any time point relative to implant, abutment, or tooth placement, or did not specify a time period for eligible failures. Three studies^26,28,33^ reported implant failures occurring before and up to abutment placement, and 1 study4 included cases of osseointegration failure leading to implant removal (rather than implant failure per se) that occurred before tooth loading. No studies included peri-implantitis as an outcome of interest.

All studies were rated as moderate risk of bias (see Appendix C in the Supplemental Materials for full risk of bias ratings). The most severe risk of bias, present in 3 studies,^4,30,33^ was failure to control for potential confounding in reported analyses. Other studies controlled for some, but not all, likely confounders (eg, patient age, sex, smoking status, bone quality, systemic diseases such as diabetes and osteoporosis, etc), typically by including potential confounders as covariates in statistical models. These studies were considered at moderate risk of bias from confounding.

Several studies were at risk of selection biases because eligibility was limited only to observations with complete data, or because participants who lost fewer than half of their implants, or any implants lost after an initial failure, were excluded. Some studies also did not clearly describe how antidepressant use or implant failure was determined or defined. Studies of mental health conditions^27,30,31^ did not adequately describe the diagnostic status, severity, or duration of conditions, or relied on diagnostic data collected through methods subject to bias (eg, provider judgment of a mental health condition as the reason for implant failure).

Finally, some studies prescribed prophylactic antibiotics to implant recipients, and recipients in at least 1 study^13^ were also participating in a post-implant support program. Both factors could have attenuated observed associations between antidepressant use and implant failure risk in those studies, and inconsistency in the delivery and uptake of these preventive approaches across studies may be a source of heterogeneity in implant failure risk.

Table 1 Characteristics of Included Primary Studies

Study | Country | Sample Size # Implants | Population | Exposures | Outcomes Assessed
Alsaadi 2007^26^ | Belgium | N=2004 (6946 implants) | Consecutive patients treated with endosseous implants | Antidepressant, no antidepressant | Early implant failure (before and up to abutment connection)
Alsaadi 2008^33^ | Belgium | N=283 (720 implants) | Consecutive patients treated with endosseous implants | Antidepressant, no antidepressant | Early implant failure (before and up to abutment connection)
Altay 2018^4^ | Turkey | N=631 (2055 implants) | All patients rehabilitated with dental implants presenting with no systemic conditions and not taking any medications other than SSRIs for psychiatric disorders | SSRI, no SSRI | Early osseointegration failure (before tooth loading)
Block 2021^31^ | US | N=224 (224 implants) | All patients with 1 or more implants removed by senior author. Failed sample included 1 implant per patient case and was the first implant placed or failed. Control group was a consecutive series of patients with implant placement in 2012 who did not have implant failure | Depression, no depression | Implant failure within 1 year, 1–4 years,^*^ and more than 4 years
Carr 2019^20^ | US | N=5456 (5456 implants) | All patients who received their first dental implant | SSRI, no SSRI, other SSRI type (history of use, active SSRI use, follow-up SSRI use) | Implant failure
Chatzopoulos 2018^27^ | US | N=4519 (4519 implants) | Patients at least 18 years of age with a complete demographic and medical history who received root canal treatment or implant treatment | Depression or anxiety, no depression or anxiety | Implant failure
Chrcanovic 2016^28^ | Sweden | N=2670 (10096 implants) | Patients consecutively treated with implant-supported prostheses | Antidepressant, no antidepressant | Implant failure (up to^*^ and after the abutment connection)
Chrcanovic 2017^29^ | Sweden | N=300 (931 implants) | Patients consecutively treated with implant-supported prostheses. SSRI group had to be taking only SSRIs and no other medication and be without any other systemic condition | SSRI, no SSRI | Implant failure
Deepa 2018^32^ | India | N=352 (680 implants) | Patients rehabilitated with dental implants | SSRI, no SSRI | Implant failure (due to fracture of implant, prosthesis screw fracture, and/or loosening of screw, or peri-implantitis)
Ekfeldt 2001^30^ | Sweden | N=54 (301 implants) | Patients completely edentulous in the maxilla. Patients in study group lost at least half of their implants. Control group had lost no implants and was matched to study group on age, gender, number of implants, and timeframe of implant placement | Psychological illness judged as reason for failure, psychological illness not judged as reason for failure | Implant failure before and after loading
Hakam 2021^13^ | US | N=771 (1820 implants) | Patients ≥ 18 who received dental implants taking at least 1 type of antidepressant, or were systematically healthy or had mild systemic disease without history of antidepressant use | Antidepressant, no antidepressant, other antidepressant | Implant failure
Wu 2014^21^ | Canada | N=490 (916 implants) | Patients treated with dental osseointegrated prosthesis. Patients were excluded if they had a severe systemic disease, were pregnant, or had a medical disorder known to substantially affect bone metabolism | SSRI, no SSRI | Implant failure

Notes.

* Only time point for which relevant data were reported.

Abbreviations. SSRI=selective serotonin reuptake inhibitor.

### MAIN FINDINGS

#### Antidepressant Use

Across 9 available studies^4,13,20,21,26,28,29,32,33^ (N = 25,364 implants^i^), approximately 1 in every 26 implants failed; about 1 in 9 implants failed among implant recipients on antidepressant medications, in contrast to 1 in every 34 among recipients not using antidepressants. Based on moderate-strength evidence from these studies, antidepressant users experience significantly greater risk of implant failure than non-users (RR_Mean_ = 1.60, 95% CI [1.21, 2.13]). When only studies^13,20,21,26,28,29^ that used methods to control for potential confounders are pooled, the mean increase in risk is somewhat smaller in magnitude and is no longer statistically significant (RR_Mean_ = 1.40, 95% CI [0.97, 2.03]).

i The analytic sample size was N = 24,315 implants because 1 study^13^ reported findings at the patient level rather than implant level (ie, information from implant failures beyond an initial failure is masked).

Results of available studies are consistent in direction but differ in magnitude (Figure 2). Variability in implant failure risk may result from differences in exposures (SSRIs only or SSRIs and other antidepressants), selection of patient samples (differences in patient and implant eligibility criteria, extent of incomplete records, use of consecutive versus nonconsecutive records, etc), and degree of uncontrolled confounding. The extent of heterogeneity (95% PI [0.87, 2.94]) indicates future studies are likely to observe elevated implant failure risk among recipients using antidepressants compared with non-users (because most values in the interval are greater than 1). Whether differences in risk would be small or very large is unclear, however.

Figure 2 Implant Failure Risk Associated with Antidepressant Use

Notes. Gray error bars around summary estimate diamonds correspond to 95% prediction intervals.

Abbreviations. AD=antidepressant.

Two studies^26,28^ conducted in northern Europe merit further discussion. In addition to being the largest studies identified (N = 5,759–7,027 implants), both studies controlled for a similar set of likely confounders (including smoking status, bone quality and quantity at the implant site, and implant characteristics), eliminated implant failure timing as a potential source of heterogeneity by focusing only on failures that occurred in the period between implant and abutment placement, and used comparable analytic approaches to account for clustering of implants within patients. Both studies also limited selection bias risk by counting all failures rather than only the first, and were among the few studies that explicitly reported use of data from consecutively treated patients (a strategy that may increase the representativeness of the final sample).

Findings from each study are similar in magnitude and suggest antidepressant use may be associated with elevated risk of early implant failure, although both reported results were nonsignificant (adjusted odds ratio = 1.28, 95% CI [0.64, 2.58];^26^ 1.74, 95% CI [0.86, 3.54]^28^). When pooled,^ii^ the mean risk estimate (RR_Mean_ = 1.22, 95% CI [1.07, 1.40]) is more precise than study-level results, and compared with the risk estimate produced by pooling all available evidence, is consistent in direction and significance but smaller in magnitude. Evidence from only the most rigorous available studies, therefore, indicates that antidepressant use at the time of implant placement is associated with an approximately 20% increase in risk of early implant failure.

ii After conversion to RRs for meta-analyses, ratio values were 1.13 and 1.32, respectively.

Finally, no study directly assessed the association between antidepressant use or mental health conditions and peri-implantitis risk, and evidence is therefore insufficient to make conclusions. One included study^32^ (N = 680 implants) reported that 24% (6/25) of implant failures among SSRI users were attributable to peri-implantitis compared with 14% (3/21) of failures in SSRI non-users.

##### Antidepressant Type

Despite their relative rigor, the above studies^26,28^ did not report details of the antidepressants used by patients in the exposure group, so it is unclear if the observed differences in implant failures in those studies are attributable to certain classes of antidepressants. Six other studies^4,13,20,21,29,32^ (N = 10,770 implants) provide evidence on SSRIs specifically, and when findings are pooled, SSRI use at the time of implant placement is associated with increased risk of implant failure (RR_Mean_ = 1.84, 95% CI [1.17, 2.88]). This result includes studies that implemented some level of control for confounding and those that reported only unadjusted results, and considerable heterogeneity is evident (95% PI [0.65, 5.20]). Pooling evidence from the subset of studies^20,21,29^ that reported adjusted findings produces a similar, albeit more imprecise, risk estimate (RR_Mean_ = 1.77, 95% CI [0.29, 10.95]).

Finally, 1 study^13^ reported implant failure risk among patients (N = 771) using different classes of antidepressants. Compared to patients who took no antidepressants, implant failure was significantly more likely among patients who used serotonin-norepinephrine reuptake inhibitors (SNRIs; RR = 8.00, 95% CI [3.53, 18.07]) or tricyclic antidepressants (RR = 8.53, 95% CI [2.60, 28.05]). The likelihood of implant failure for patients using these classes of antidepressants was much greater than for SSRI users in this study (RR = 1.63, 95% CI [0.51, 5.18]), but it should be noted that these risk estimates were not adjusted for potential confounders. Moreover, the total number of patients included in the study who were on SSRIs, SNRIs, or tricyclic antidepressants was small (58 of 771 patients), and implant failures were rare in all subgroups (ranging from 1 to 4 patients with failures per group).

##### Failure Timing

As noted, antidepressant/SSRI groups in included studies comprised patients who were using antidepressants prior to (or at the time of) implant placement. One study^20^ also analyzed implant failures in a group of patients (N = 304) with no history of SSRI use who began using SSRIs during the follow-up period. Failure risk was inconsistent across the 5 types of SSRIs included in the study (median HR = 1.25, range = 0.24–2.09), and all results were nonsignificant.

#### Mental Health Conditions

Three studies examined the risk of implant failure associated with depression,^31^ depression or anxiety,^27^ or any mental health condition judged by a provider to be the reason for implant failure.^30^ Although more than 1 study was available, we concluded there is insufficient evidence to draw conclusions about the effect of mental health conditions on risk of implant failure because inconsistency in, or lack of clarity on, exposures, outcome definitions, and other methodological features limited the comparability of studies.

One identified study31 included 224 patients with 1 or more implants, and reported that depression was significantly associated with occurrence of implant failures 1 to 4 years after implant placement (OR = 5.28, 95% CI [1.40, 19.82]; adjusted for patient age, gender, smoking status, and diagnosis with osteoporosis). A second study^27^ (N = 4,519 implants) examined depression, anxiety, and other potential risk factors for implant failures during the period each patient was observed (mean observation period = 34 months [SD = 19.33 months]). The study found that anxiety was significantly associated with implant failures (HR = 1.55, 95% CI [1.15, 2.09]; adjusted for root canal treatment history and patient age), and also reported that the majority of implant failures (59%) occurred in the first year after placement. In the final study30 (N = 251 implants), clinicians of patients with implant failures attributed the failures to poor quality or lack of supportive bone, heavy smoking, bruxism, psychological reasons, or the influence of other illnesses (eg, diabetes). Failures of 12 implants in 2 patients were attributed to psychological reasons (personal grief from the death of a spouse or child).

## DISCUSSION

Evidence on the association between antidepressant use and implant failure risk is moderate strength and relies on observational studies of varying sizes and rigor. As a whole, available evidence suggests that implant failures are more likely in patients using antidepressants at the time of implant placement than in patients not using antidepressants. The degree to which implant failure risk is elevated varies across studies, but findings from the most rigorous studies indicate that antidepressant use at the time of implant placement is associated with an approximately 20% increase in risk of early implant failure. A limited number of studies investigated whether the presence of mental health conditions increases implant failure risk; although studies reported associations between depression or anxiety and implant failure, evidence from these studies is insufficient to make conclusions. Moreover, the mechanism by which mental health conditions influence implant failure risk remains unclear. No studies examined the impact of antidepressant use or mental health conditions on peri-implantitis risk.

Our estimate of mean implant failure risk associated with antidepressant use is smaller than that reported in a recently published meta-analysis^2^ of 5 included studies^4,21,29,32,33^ (RR_Mean_ = 3.73, 95% CI [1.85, 7.52]). An analysis of the same studies using our data and methodology, not reported above, results in smaller risk estimate (RR_Mean_ = 2.44, 95% CI [2.10, 2.84]). This discrepancy may be attributable, at least in part, to the use of raw counts of implant failures for all studies in the published meta-analysis, compared with our use of ratios adjusted for potential confounders reported by 2 studies.^21,29^ Additionally, although both analyses used random-effects models, the authors of the published review appear to have used a different method to estimate heterogeneity than we employed, and did not report use of statistical adjustments to account for the small number of pooled studies and uncertainty in estimates of heterogeneity. Differences in these aspects of the analytic approaches could impact the width of reported confidence intervals.

### LIMITATIONS

Limitations of our review methods include use of a second reviewer check during study selection, data abstraction, and quality assessment rather than dual independent review. Additionally, both statistical precision and heterogeneity can be poorly estimated in small meta-analyses. We took steps to ameliorate these concerns, namely use of corrections to better account for uncertainty in the estimation of heterogeneity as well as cluster-robust methods to calculate confidence intervals, but some caution should be used in interpreting reported meta-analytic confidence intervals and prediction intervals.

### FUTURE RESEARCH

Loss of implants in the early period between implant placement and abutment connection is consistent with the purported mechanism by which antidepressant use elevates failure risk. SSRIs and other antidepressants influence the formation of bone,^2,12^ and consequently would hamper the initial osseointegration process (leading to earlier failure) rather than compromise a fully integrated implant. It is possible that other processes, including mechanical overloading of an implant through bruxism, could increase failure risk at later stages.^8^ Conceivably, mental health conditions such as anxiety could be linked to bruxism^34^ (which may, in turn, elevate implant failure risk), but we found no research that explicitly examined this pathway, nor comparable pathways for other mental health conditions (eg, a link between depression, neglect of oral health, and implant failure).

Research is needed that would clarify relationships between mental health conditions, behavioral responses, and implant outcomes across a wide range of mental health conditions. In the nearer term, Veterans may benefit from research on, and implementation of, screening methods that would facilitate earlier detection of known and likely implant failure risk factors in implant candidates, as well as osseointegration issues in implant recipients. Particularly in older adults like those routinely served by the VA, there have been calls to more aggressively screen implant candidates for prior medical and social risk factors and to better account for these factors in individual treatment plans.^3^ A screening tool for peri-implant disease risk factors^35^ has been recently published, and although this tool lacks an antidepressant use or mental health condition domain, one could potentially be added and evaluated within VA clinical settings.

Additionally, systematic reviews^36,37^ of evidence on tailored peri-implant maintenance therapy (PIMT; comprising regular prophylaxis, evaluation of implant healing, and/or instruction on oral hygiene) have identified benefits of these programs in addressing oral health-related risk factors for implant failure (eg, inflammation and bone loss). Because PIMT may be helpful in limiting the impacts of these risk factors regardless of their etiology, it may constitute a promising innovation to be investigated for implementation in the VA. In the context of VA integrated care, it is conceivable that benefits of screening and maintenance programs might be enhanced with linkages to other available supports such as smoking cessation assistance, nutrition support therapy, and mental health and substance use treatment services.

### CONCLUSIONS

Moderate-strength evidence indicates that antidepressant use is likely associated with elevated risk of implant failure. Available studies provide suggestive evidence that implants may be at greater risk of failing before abutment placement, which is consistent with the purported mechanism by which antidepressants influence the osseointegration process and the likelihood of implant failure. Although antidepressant use alone may increase the risk of implant failure, many failures could be the result of a complex array of risk factors. Consequently, Veterans may benefit from approaches to better detect risk factors for implant failure prior to implant placement, as well as from future research on the effectiveness and feasibility of tailored periimplant maintenance programs that could enable prevention and earlier detection and treatment of oral health-related risk factors for implant failure.

## REFERENCES

1. Mayo Clinic. Dental implant surgery. Mayo Foundation for Medical Education and Research. https://www.mayoclinic.org/tests-procedures/dental-implant-surgery/about/pac-20384622. Published 2019. Accessed June 2022.
2. Silva CC G, Dos Santos MS, Monteiro J, de Aguiar Soares Carneiro SC, do Egito Vasconcelos BC. Is there an association between the use of antidepressants and complications involving dental implants? A systematic review and meta-analysis. Int J Oral Maxillofac Surg. 2021;50(1):96–103.32534847
3. Stanford CM. Dental implants. A role in geriatric dentistry for the general practice? J Am Dent Assoc. 2007;138 Suppl:34S-40S.17761844
4. Altay MA, Sindel A, Ozalp O, Does the Intake of Selective Serotonin Reuptake Inhibitors Negatively Affect Dental Implant Osseointegration? A Retrospective Study. Journal of Oral Implantology. 2018;44(4):260–265.29517407
5. Pye AD, Lockhart DE, Dawson MP, Murray CA, Smith AJ. A review of dental implants and infection. J Hosp Infect. 2009;72(2):104–110.19329223
6. Esposito M, Grusovin MG, Chew YS, Coulthard P, Worthington HV. Interventions for replacing missing teeth: 1- versus 2-stage implant placement. Cochrane Database of Systematic Reviews. 2009(3).
7. Chen J, Cai M, Yang J, Aldhohrah T, Wang Y. Immediate versus early or conventional loading dental implants with fixed prostheses: A systematic review and meta-analysis of randomized controlled clinical trials. J Prosthet Dent. 2019;122(6):516–536.31421892
8. Oh SL, Shiau HJ, Reynolds MA. Survival of dental implants at sites after implant failure: A systematic review. J Prosthet Dent. 2020;123(1):54–60.31027959
9. Dreyer H, Grischke J, Tiede C, Epidemiology and risk factors of peri-implantitis: A systematic review. J Periodontal Res. 2018;53(5):657–681.29882313
10. Kullar AS, Miller CS. Are There Contraindications for Placing Dental Implants? Dent Clin North Am. 2019;63(3):345–362.31097131
11. Naseri R, Yaghini J, Feizi A. Levels of smoking and dental implants failure: A systematic review and meta-analysis. Journal of Clinical Periodontology. 2020;47(4):518–528.31955453
12. Tarfa RA, Melder K, Mady LJ, Eibling D. Is mandibular osteomyelitis a sequela of SSRI-induced dental implant failure? A systematic review & case report. American Journal of Otolaryngology. 2022;43(1):103236.34583289
13. Hakam AE, Vila G, Duarte PM, Effects of different antidepressant classes on dental implant failure: A retrospective clinical study. Journal of Periodontology. 2021;92(2):196–204.32725908
14. Peruzzo DC, Benatti BB, Ambrosano GM B, A Systematic Review of Stress and Psychological Factors as Possible Risk Factors for Periodontal Disease. Journal of Periodontology. 2007;78(8):1491–1504.17668968
15. Warren KR, Postolache TT, Groer ME, Pinjari O, Kelly DL, Reynolds MA. Role of chronic stress and depression in periodontal diseases. Periodontology 2000. 2014;64(1):127–138.24320960
16. Iacopino AM. Relationship between stress, depression and periodontal disease. J Can Dent Assoc. 2009;75(5):329–330.19536930
17. Hayden JA, van der Windt DA, Cartwright JL, Pierre Côté D, Bombardier C. Assessing Bias in Studies of Prognostic Factors. Annals of Internal Medicine. 2013;158(4):280–286.23420236
18. Berkman ND, Lohr KN, Ansari M, Grading the Strength of a Body of Evidence When Assessing Health Care Interventions for the Effective Health Care Program of the Agency for Healthcare Research and Quality: An Update. Rockville, MD: Agency for Healthcare Research and Quality;2013.
19. VanderWeele TJ. Optimal approximate conversions of odds ratios and hazard ratios to risk ratios. Biometrics. 2020;76(3):746–752.31808145
20. Carr AB, Gonzalez RL V, Jia L, Lohse CM. Relationship between Selective Serotonin Reuptake Inhibitors and Risk of Dental Implant Failure. Journal of Prosthodontics. 2019;28(3):252–257.30637850
21. Wu X, Al-Abedalla K, Rastikerdar E, Selective serotonin reuptake inhibitors and the risk of osseointegrated implant failure: a cohort study. Journal of Dental Research. 2014;93(11):1054–1061.25186831
22. Borenstein M, Higgins JP, Hedges LV, Rothstein HR. Basics of meta-analysis: I2 is not an absolute measure of heterogeneity. Res Synth Methods. 2017;8(1):5–18.28058794
23. Parr NJ, Schweer-Collins ML, Darlington TM, Tanner-Smith EE. Meta-analytic approaches for examining complexity and heterogeneity in studies of adolescent development. J Adolesc. 2019;77:168–178.31739275
24. Knapp G, Hartung J. Improved tests for a random effects meta-regression with a single covariate. Statistics in Medicine. 2003;22(17):2693–2710.12939780
25. Viechtbauer W. metafor: Meta-analysis package for R. The Comprehensive R Archive Network. https://cran.r-project.org/web/packages/metafor/index.html. Published 2020. Accessed October 2020.
26. Alsaadi G, Quirynen M, Komárek A, van Steenberghe D. Impact of local and systemic factors on the incidence of oral implant failures, up to abutment connection. Journal of Clinical Periodontology. 2007;34(7):610–617.17433044
27. Chatzopoulos GS, Koidou VP, Lunos S, Wolff LF. Implant and root canal treatment: Survival rates and factors associated with treatment outcome. Journal of Dentistry. 2018;71:61–66.29499242
28. Chrcanovic BR, Kisch J, Albrektsson T, Wennerberg A. Factors Influencing Early Dental Implant Failures. Journal of Dental Research. 2016;95(9):995–1002.27146701
29. Chrcanovic BR, Kisch J, Albrektsson T, Wennerberg A. Is the intake of selective serotonin reuptake inhibitors associated with an increased risk of dental implant failure? International Journal of Oral & Maxillofacial Surgery. 2017;46(6):782–788.28222946
30. Ekfeldt A, Christiansson U, Eriksson T, A retrospective analysis of factors associated with multiple implant failures in maxillae. Clinical Oral Implants Research. 2001;12(5):462–467.11564105
31. Block MS, Christensen BJ, Mercante DE, Chapple AG. What Factors Are Associated With Implant Failure? Journal of Oral & Maxillofacial Surgery. 2021;79(1):91–97.32956618
32. Deepa, Mujawar K, Dhillon K, Jadhav P, Das I, Singla YK. Prognostic Implication of Selective Serotonin Reuptake Inhibitors in Osseointegration of Dental Implants: A 5-year Retrospective Study. Journal of Contemporary Dental Practice [Electronic Resource]. 2018;19(7):842–846.
33. Alsaadi G, Quirynen M, Michiles K, Teughels W, Komárek A, van Steenberghe D. Impact of local and systemic factors on the incidence of failures up to abutment connection with modified surface oral implants. Journal of Clinical Periodontology. 2008;35(1):51–57.18034851
34. Polmann H, Domingos FL, Melo G, Association between sleep bruxism and anxiety symptoms in adults: A systematic review. Journal of Oral Rehabilitation. 2019;46(5):482–491.30805947
35. Heitz-Mayfield LJ A, Heitz F, Lang NP. Implant Disease Risk Assessment IDRA-a tool for preventing peri-implant disease. Clin Oral Implants Res. 2020;31(4):397–403.32003037
36. Monje A, Aranda L, Diaz KT, Impact of Maintenance Therapy for the Prevention of Peri-implant Diseases:A Systematic Review and Meta-analysis. Journal of Dental Research. 2016;95(4):372–379.26701350
37. Ramanauskaite A, Tervonen T. The Efficacy of Supportive Peri-Implant Therapies in Preventing Peri-Implantitis and Implant Loss: a Systematic Review of the Literature. J Oral Maxillofac Res. 2016;7(3):e12.27833737

## Supplemental Materials

Download Supplemental Materials PDF

### APPENDIX A SEARCH STRATEGY

#### SYSTEMATIC REVIEWS

1. Search for current systematic reviews (limited to last 7 years); Date Searched: 03-17-22
A. Bibliographic Databases: | # | Search Statement | Results
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 1 | Dental Restoration Failure/ | 8894
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 2 | Dental Implantation, Endosseous/ae | 1455
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 3 | Dental Implants/ae | 2346
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 4 | (peri?implantitis or (implant adj1 (loss* or fail*))).mp. | 7290
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 5 | exp Mental Disorders/ | 1356477
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 6 | exp Behavioral Symptoms/ | 413089
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 7 | exp Serotonin Uptake Inhibitors/ | 44543
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 8 | exp Substance-Related Disorders/ | 298237
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 9 | (depression or anxiety or ptsd or post?traumatic stress or bipolar or schizophrenia).mp. | 819042
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 10 | 1 or 2 or 3 or 4 | 17040
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 11 | 5 or 6 or 7 or 8 or 9 | 2006410
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 12 | 10 and 11 | 110
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 13 | (systematic review.ti. or meta-analysis.pt. or meta-analysis.ti. or systematic literature review.ti. or this systematic review.tw. or pooling project.tw. or (systematic review.ti,ab. and review.pt.) or meta synthesis.ti. or meta-analy*.ti. or integrative review.tw. or integrative research review.tw. or rapid review.tw. or umbrella review.tw. or consensus development conference.pt. or practice guideline.pt. or drug class reviews.ti. or cochrane database syst rev.jn. or acp journal club.jn. or health technol assess.jn. or evid rep technol assess summ.jn. or jbi database system rev implement rep.jn. or (clinical guideline and management).tw. or ((evidence based.ti. or evidence-based medicine/ or best practice*.ti. or evidence synthesis.ti,ab.) and (((review.pt. or diseases category/ or behavior.mp.) and behavior mechanisms/) or therapeutics/ or evaluation studies.pt. or validation studies.pt. or guideline.pt. or pmcbook.mp.)) or (((systematic or systematically).tw. or critical.ti,ab. or study selection.tw. or ((predetermined or inclusion) and criteri*).tw. or exclusion criteri*.tw. or main outcome measures.tw. or standard of care.tw. or standards of care.tw.) and ((survey or surveys).ti,ab. or overview*.tw. or review.ti,ab. or reviews.ti,ab. or search*.tw. or handsearch.tw. or analysis.ti. or critique.ti,ab. or appraisal.tw. or (reduction.tw. and (risk/ or risk.tw.) and (death or recurrence).mp.)) and ((literature or articles or publications or publication or bibliography or bibliographies or published).ti,ab. or pooled data.tw. or unpublished.tw. or citation.tw. or citations.tw. or database.ti,ab. or internet.ti,ab. or textbooks.ti,ab. or references.tw. or scales.tw. or papers.tw. or datasets.tw. or trials.ti,ab. or meta-analy*.tw. or (clinical and studies).ti,ab. or treatment outcome/ or treatment outcome.tw. or pmcbook.mp.))) not (letter or newspaper article).pt. | 506300
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to March 16, 2022 | 14 | 12 and 13 | 18
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to March 16, 2022 | 1 | Dental Restoration Failure.kw. | 14
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to March 16, 2022 | 2 | Endosseous Dental Implantation.kw. | 0
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to March 16, 2022 | 3 | Dental Implants.kw. | 11
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to March 16, 2022 | 4 | (peri?implantitis or (implant adj1 (loss* or fail*))).mp. | 38
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to March 16, 2022 | 5 | Mental Disorders.kw. | 70
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to March 16, 2022 | 6 | Behavioral Symptoms.kw. | 2
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to March 16, 2022 | 7 | Serotonin Uptake Inhibitors.kw. | 54
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to March 16, 2022 | 8 | Substance-Related Disorders.kw. | 34
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to March 16, 2022 | 9 | (depression or anxiety or ptsd or post?traumatic stress or bipolar or schizophrenia).mp. | 3224
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to March 16, 2022 | 10 | 1 or 2 or 3 or 4 | 50
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to March 16, 2022 | 11 | 5 or 6 or 7 or 8 or 9 | 3242
| 12 | 10 and 11 | 10

1. Search for current systematic reviews (limited to last 7 years); Date Searched: 03-17-22
B. Non-bibliographic databases | Evidence | Results
AHRQ: evidence reports, technology assessments, U.S Preventative Services Task Force Evidence Synthesis | http://www.ahrq.gov/research/findings/evidence-based-reports/search.html; Search: dental implants; peri-implantitis; mental health; substance use | 0
CADTH | https://www.cadth.ca; Search: dental implants; peri-implantitis; mental health; substance use | 0
ECRI Institute | https://guidelines.ecri.org/; Search: dental implants; peri-implantitis | 0
HTA: Health Technology Assessments (UP TO 2016) | http://www.ohsu.edu/xd/education/library/; See CDSR search above | 0
NHS Evidence | http://www.evidence.nhs.uk/default.aspx; Search: dental implants; peri-implantitis; mental health; substance use | 0
EPPI-Centre | http://eppi.ioe.ac.uk/cms/Default.aspx?tabid=62; Use browser search function [CNTL + F] for keyword search; Search: dental implants; peri-implantitis; mental health; substance use | 0
NLM | http://www.ncbi.nlm.nih.gov/books; Search: dental implants; peri-implantitis; mental health; substance use; Section 5: Pain, Mental Illness, Substance Use, and Oral Health. Oral Health in America: Advances and Challenges [Internet]. Bethesda (MD): National Institute of Dental and Craniofacial Research. 2021 Dec. https://www.ncbi.nlm.nih.gov/books/NBK578300/ | 1
VA Products - VATAP, PBM and HSR&D publications | A. http://www.hsrd.research.va.gov/research/default.cfm; B. http://www.research.va.gov/research_topics/; Search: dental implants; peri-implantitis; mental health; substance use | 0

2. Search for systematic reviews currently under development (includes forthcoming reviews & protocols); Date Searched: 03-17-22
D. Under development: | Evidence: | Results
AHRQ topics in development (EPC Status Report) | Email Charli Armstrong Charlotte.Armstrong1@va.gov | 0
PROSPERO (SR registry) | http://www.crd.york.ac.uk/PROSPERO/; Caio Silva, Marcelo Santos, João Monteiro, Suzana Carneiro. Is there an association between antidepressant use and complications of dental implants? A systematic review. PROSPERO 2019 CRD42019119995 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42019119995 | 1

#### PRIMARY STUDIES

3. Search for primary literature; Date searched: 03-17-22
MEDLINE [Ovid MEDLINE(R) ALL 1946 to March 16, 2022]
# | Search Statement | Results
1 | Dental Restoration Failure/ | 8894
2 | Dental Implantation, Endosseous/ae | 1455
3 | Dental Implants/ae | 2346
4 | (peri?implantitis or (implant adj1 (loss* or fail*))).mp. | 7290
5 | exp Mental Disorders/ | 1356477
6 | exp Behavioral Symptoms/ | 413089
7 | exp Serotonin Uptake Inhibitors/ | 44543
8 | exp Substance-Related Disorders/ | 298237
9 | (depression or anxiety or ptsd or post?traumatic stress or bipolar or schizophrenia).mp. | 819042
10 | 1 or 2 or 3 or 4 | 17040
11 | 5 or 6 or 7 or 8 or 9 | 2006410
12 | 10 and 11 | 110
CINAHL
# | Search Statement | Results
1 | (MH “Dental Restoration, Permanent+”) OR (MH “Dental Restoration, Temporary”) | 9522
2 | (MH “Dental Implantation+/AE”) | 908
3 | (MH “Dental Implants/AE”) | 737
4 | TX (peri?implantitis or (implant N1 (loss* or fail*))) | 4156
5 | (MH “Mental Disorders+”) | 622744
6 | (MH “Behavioral Symptoms+”) | 642851
7 | (MH “Serotonin Uptake Inhibitors+”) | 12310
8 | (MH “Substance Use Disorders+”) | 178806
9 | TX (depression or anxiety or ptsd or post?traumatic stress or bipolar or schizophrenia) | 465498
10 | 1 or 2 or 3 or 4 | 14244
11 | 5 or 6 or 7 or 8 or 9 | 1093874
12 | 10 and 11 | 638
PsycINFO [APA PsycInfo 1806 to March Week 2 2022]
# | Search Statement | Results
1 | dental restoration failure.mp. | 2
2 | dental implantation.mp. | 9
3 | dental implants.mp. | 28
4 | (peri?implantitis or (implant adj1 (loss* or fail*))).mp. | 6
5 | exp Mental Disorders/ | 924768
6 | exp Behavior Disorders/ | 61373
7 | exp Serotonin Reuptake Inhibitors/ | 12883
8 | exp “Substance Use Disorder”/ | 138272
9 | (depression or anxiety or ptsd or post?traumatic stress or bipolar or schizophrenia).mp. | 668531
10 | 1 or 2 or 3 or 4 | 42
11 | 5 or 6 or 7 or 8 or 9 | 1223115
12 | 10 and 11 | 8

### APPENDIX B EXCLUDED STUDIES

Exclude reasons: 1=Ineligible population, 2=Ineligible intervention, 3=Ineligible comparator, 4=Ineligible outcome, 5=Ineligible timing, 6=Ineligible study design, 7=Ineligible publication type, 8=Outdated or ineligible systematic review.

Citation | Exclude Reason
SSRIs linked to implant failure. Dental Nursing. 2014;10(10):556–556. | E7
ANTIDEPRESSANTS MAY BE LINKED TO IMPLANT FAILURE RISK, RESEARCHERS REPORT. Journal of the American Dental Association (JADA). 2014;145(10):1016–1016. | E7
SELECTIVE SEROTONIN REUPTAKE INHIBITORS AND IMPLANT FAILURE. Explorer (08947929). 2019;45(7):3–3. | E10
Medication impact on dental implant failure. Dental Abstracts. 2019;64(4):273–274. | E10
Anitua E, Orive G, Aguirre JJ, Ardanza B, Andía I. 5-year clinical experience with BTI dental implants: risk factors for implant failure. Journal of Clinical Periodontology. 2008;35(8):724–732.18616758 | E2
Brignardello-Petersen R. LOW RATE OF EARLY IMPLANT FAILURE IS CONFIRMED, BUT SMOKING AND ANTIDEPRESSANTS ARE SHOWN TO BE RISK FACTORS. Journal of the American Dental Association (JADA). 2017;148(4):e2–e2.28088262 | E7
Chappuis V, Avila-Ortiz G, Araujo MG, Monje A. Medication-related dental implant failure: Systematic review and meta-analysis. Clinical Oral Implants Research. 2018;29 Suppl 16:55–68. | E8
Chatzopoulos GS, Koidou VP, Lunos S, Wolff LF. Implant and root canal treatment: Survival rates and factors associated with treatment outcome. Journal of Dentistry. 2018;71:61–66.29499242 | E8
Cheng LL. Systemic Intake of Proton Pump Inhibitors and Selective Serotonin Reuptake Inhibitors May Be Associated With Implant Failure. The Journal of Evidencebased Dental Practice. 2020;20(3):101466. | E7
Derks J, Håkansson J, Wennström JL, Tomasi C, Larsson M, Berglundh T. Effectiveness of implant therapy analyzed in a Swedish population: early and late implant loss. Journal of Dental Research. 2015;94:44S–51S.25503901 | E2
Gupta B, Acharya A, Pelekos G, Gopalakrishnan D, Kolokythas A. Selective serotonin reuptake inhibitors and dental implant failure-A significant concern in elders? Gerodontology. 2017;34(4):505–507.28744899 | E7
Güven SŞ, Cabbar F, Güler N. Local and systemic factors associated with marginal bone loss around dental implants: a retrospective clinical study. Quintessence International. 2020;51(2):128–141.31942574 | E2
Jing H, Baohong Z, Chunfu D, Dehao S, Chong Z. Assessment of Implant Cumulative Survival Rates in Sites with Different Bone Density and Related Prognostic Factors: An 8-Year Retrospective Study of 2,684 Implants. International Journal of Oral & Maxillofacial Implants. 2015;30(2):360–371.25830396 | E2
Jung RE, Al-Nawas B, Araujo M, Group 1 ITI Consensus Report: The influence of implant length and design and medications on clinical and patient-reported outcomes. Clinical Oral Implants Research. 2018;29 Suppl 16:69–77.30328189 | E7
Kim IH, Kuk TS, Park SY, Choi YS, Kim HJ, Seo KS. Prognosis following dental implant treatment under general anesthesia in patients with special needs. Journal of Dental Anesthesia & Pain Medicine. 2017;17(3):205–213.29090251 | E2
Koldsland OC, Scheie AA, Aass AM. Prevalence of implant loss and the influence of associated factors. Journal of Periodontology. 2009;80(7):1069–1075.19563286 | E2
Liddelow G, Klineberg I. Patient-related risk factors for implant therapy. A critique of pertinent literature. Australian Dental Journal. 2011;56(4):417–426.22126353 | E2
Marchio V, Derchi G, Cinquini C, Tissue level implants in healthy versus medically compromised patients: a cohort comparative study. Minerva Stomatologica. 2020;69(5):295–301.32407061 | E2
McDermott NE, Chuang S, Woo VV, Dodson TB. Complications of dental implants: identification, frequency, and associated risk factors. International Journal of Oral & Maxillofacial Implants. 2003;18(6):848–855.14696660 | E2
Moy PK, Medina D, Shetty V, Aghaloo TL. Dental implant failure rates and associated risk factors. International Journal of Oral & Maxillofacial Implants. 2005;20(4):569–577.16161741 | E2
Mundt T, Mack F, Schwahn C, Biffar R. Private practice results of screw-type tapered implants: survival and evaluation of risk factors. International Journal of Oral & Maxillofacial Implants. 2006;21(4):607–614.16955613 | E2
Paquette DW, Brodala N, Williams RC. Risk factors for endosseous dental implant failure. Dental Clinics of North America. 2006;50(3):361–374.16818020 | E2
Roos-Jansåker A, Renvert H, Lindahl C, Renvert S. Nine- to fourteen-year follow-up of implant treatment. Part III: factors associated with peri-implant lesions. Journal of Clinical Periodontology. 2006;33(4):296–301.16553639 | E4
Schimmel M, Srinivasan M, McKenna G, Muller F. Effect of advanced age and/or systemic medical conditions on dental implant survival: A systematic review and meta-analysis. Clinical Oral Implants Research. 2018;29 Suppl 16:311–330.30328186 | E7
Smith RA, Berger R, Dodson TB. Risk factors associated with dental implants in healthy and medically compromised patients. International Journal of Oral & Maxillofacial Implants. 1992;7(3):367–372.1289263 | E4
Snider J. Antidepressants may be linked to implant failure risk, researchers report. Journal of the American Dental Association. 2014;145(10):1016. | Duplicate
Susarla SM, Chuang SK, Dodson TB. Delayed versus immediate loading of implants: survival analysis and risk factors for dental implant failure. Journal of Oral & Maxillofacial Surgery. 2008;66(2):251–255.18201604 | E2
Turhani D, Ohlmeier KH, Sutter W, Kielbassa AM. Undesirable course of an oral implant rehabilitation in a patient with a long history of bulimia nervosa: case report and review of the literature. Quintessence International. 2019;50(1):68–79.30411094 | E10
Wagenberg B, Froum SJ. A retrospective study of 1,925 consecutively placed immediate implants from 1988 to 2004. International Journal of Oral & Maxillofacial Implants. 2006;21(1):71–80.16519184 | E2
Wagenberg BD, Froum SJ, Forman J, Kim S-W. A Retrospective Study of Bone-Level Stability Around 335 Hybrid Implants Placed with an Immediate or Delayed Protocol. International Journal of Periodontics & Restorative Dentistry. 2021;41(5):647–655.34547065 | E2
Zinser MJ, Randelzhofer P, Kuiper L, Zöller JE, De Lange GL. The predictors of implant failure after maxillary sinus floor augmentation and reconstruction: a retrospective study of 1045 consecutive implants. Oral Surgery, Oral Medicine, Oral Pathology & Oral Radiology. 2013;115(5):571–582.23246225 | E2

### APPENDIX C EVIDENCE TABLES

#### CHARACTERISTICS OF INCLUDED SYSTEMATIC REVIEWS

#### CHARACTERISTICS OF INCLUDED PRIMARY STUDIES

#### QUALITY ASSESSMENT OF INCLUDED PRIMARY STUDIES

#### STRENGTH OF EVIDENCE FOR INCLUDED STUDIES

### APPENDIX D PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | None
2 | 2 | Yes | None
3 | 3 | Yes | None
4 | 4 | Yes | None
5 | 5 | Yes | None
6 | 6 | Yes | None
7 | 7 | Yes | None
8 | 9 | Yes | None
Is there any indication of bias in our synthesis of the evidence?
9 | 1 | No | None
10 | 2 | No | None
11 | 3 | No | None
12 | 4 | No | None
13 | 5 | No | None
14 | 6 | No | None
15 | 7 | No | None
16 | 9 | No | None
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
17 | 1 | No | None
18 | 2 | No | None
19 | 3 | No | None
20 | 4 | No | None
21 | 5 | No | None
22 | 6 | No | None
23 | 7 | No | None
24 | 9 | No | None
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
25 | 1 | This ESP review examines the association between mental health conditions and SSRI use and peri-implantitis and dental implant failure risk. Though I do not have full details on the motivation for this review, I imagine that it would be helpful for VA dental providers to better understand (and screen for) the risks of dental implant failure and, given the resources needed to provide implants, to target this therapy for patients most likely to have positive outcomes. Alternatively, information on the risks for implant failure could potentially be used to provide support for patients undergoing the therapy, to minimize their risks of having failed implants. | Thank you for this comment. We discuss screening for risk factors in the Future Research Section.
26 | 1 | Throughout the review I wondered: are the detected associations due to the medications or to the underlying depression? Or to associated poor oral hygiene or other risks (eg, smoking, bruxism) that are more common among persons with depression or anxiety? Unfortunately, the literature does not seem to address this issue or be able to tease out such varying effects. The absence of this information in the literature severely hampers the ability to tease out the true causal factors, and in turn, limits dental providers’ ability to screen patients based on such risk factors (or provide support to address them). | We agree this is an open question that does not appear to be fully examined in existing research, as noted in the Background and Future Research sections. There are known effects of SSRIs on bone metabolism (which in turn may affect osseointegration) but the role of related or independent behavioral pathways is unclear.
27 | 1 | I did not have methodological concerns about the way the literature was reviewed or the analyses. | Thank you for this comment.
28 | 1 | The key findings section refers to evidence from 9 studies. However, in Figure 2 it becomes clear that the findings were only statistically significant in 3 of these studies. If there is a way to clarify that point in the key findings, it would help the reader better understand the evidence base. | Thank you. In a meta-analysis, evidence from all included studies is drawn upon regardless of the significance of individual study findings.
29 | 1 | What concerned me was the repeated use of statements such as “findings indicate a fairly small, but potentially meaningful, risk”. It is hard to know what this somewhat vague statement means. First, I would find it helpful to have the absolute numerical risk included in such statements. Then, put that risk into context, potentially comparing it to risks of other therapies failing. Or other risks associated with implant failure. Is this finding clinically meaningful, or not? And if so, what is its magnitude? | Thank you for this feedback. We have revised these sections and included a numerical (percentage) estimate of increased risk.
30 | 1 | Page 3, lines 53–55, it would be helpful to state the effect size of SSRIs on osseointegration learned from prior studies, to put the review findings into better perspective. | Thank you. Comparison of our findings to those of the other recent review on the topic – including comparison of effect sizes – is included in the Discussion section.
31 | 1 | Overall, it is difficult to know what to do with these findings. VA providers could screen for antidepressant use before recommending implant therapy, but given the small association with implant failure, that does not seem to be a reason to make a patient ineligible for such therapy. Added screening for oral hygiene practices, and health habits including tobacco smoking and bruxism would add some value, but it is unclear how much. In the end, programs such as the one mentioned (PIMT) might be a good option, but the evidence base is insufficient to really guide future practice, in my view. | We agree that for potential failure risk pathways that may involve behavioral sequalae of mental health conditions, the impact of screening for such conditions is unclear. We also agree that screening for the behaviors themselves may be more impactful, but it is unclear to what degree and what behavioral supports or education might be needed to garner a preventive benefit. We have added further discussion to the Future Research section.
32 | 1 | The gaps in these results might provide a good rationale for further research, however. | Thank you for this comment.
33 | 2 | Throughout, a clearer definition of what constitutes a “risk factor” for implant failure would be useful. If I’m understanding correctly, inflammation and bone loss are considered risk factors, but SSRI use or mental illnesses may be part of the etiology leading to the risk factors of interest. Perhaps the distinction is between distal and proximal risk factors (distal = SSRI, proximal = inflammation, bone loss)? | Thank you. We have clarified our discussion of these potential risk pathways in the Introduction and Executive Summary.
34 | 2 | P. 2, 2nd paragraph (and p. 15, line 3). It’s not clear to me that the current evidence suggests observational research on this topic is infeasible. Relatedly, if observational research on this topic is infeasible (the first sentence), how would research on approaches for early detection of risk factors (the second sentence) be possible? Perhaps what’s being suggested is that mental health factors could be added to implant risk assessment tools, but that the utility of adding those factors may be limited if the goal is to assess risk of peri-implantitis. | Thank you for this comment. We have clarified this section.
35 | 2 | p. 4, line 50. Which AHRQ and HSR&D databases were searched? I didn’t see these listed in Figure 1. | Full search details are listed in Appendix A.
36 | 2 | p. 5, line 52. How similar are results if you exclude converted odds ratios? Adjusted odds ratios are sensitive to choice of covariates (https://jamanetwork.com/journals/jama/article-abstract/2686777) | Thank you for this question. Four of 9 studies provided adjusted ORs, so an analysis excluding those studies would not be comparable with the reported main analysis. Prior to analyses, however, converted ratios and corresponding CIs were examined for comparability with reported values, and no values differed substantively.
37 | 2 | p. 8, line 30. In what way did studies account for confounders? That is, were covariates added into regression models, or were methods to address selection bias used? | Thank you. Further detail on studies’ adjustment methods has been added to the Literature Overview section.
38 | 3 | | None
39 | 4 | The main limitation I noted was that elements of a systematic review that are typically completed independently by at least two authors were only completed by one author e.g. (initial abstract reviews, rating of internal validity). This was acknowledged by the authors as a limitation. I do realize that this was a “rapid review” and therefore would have more limited resources available. | Although we do not do fully independent (dual) review for rapid reviews, we do utilize sequential review as noted in the Methods section. In this approach, a second reviewer corroborates all decisions about study inclusion and risk of bias/strength of evidence ratings, as well as accuracy of abstracted data. Therefore, none of these key steps is carried out by only 1 reviewer.
40 | 5 | Page 1 Ln45: Bone loss at implant site is a result of infection, and more an outcome than risk factor; Generally in dental literature, we simply say bone, as opposed to jaw bone | Thank you. We have clarified this sentence and now use “bone” rather than “jawbone”.
41 | 5 | Pg2 Ln 26: Additionally... This statement regarding maintenance is a wonderful finding from the readings and addition to this paper. Thank you!! | Thank you for this comment.
42 | 5 | Page 2 Ln 36: when you use the statement “potentially meaningful”, I would like to see that defined. I am assuming that it means the consequences could be great, but it is a key to our use of this paper, so I want it to be very clear. | See response to comment 29.
43 | 6 | NA | None
44 | 7 | I am not sure where this report would be published. I think it could be published in a dental journal like The International Journal of Oral & Maxillofacial Implants. If that action is pursued then I would recommend edits to improve dental terminology and I would be willing to help with that. The few edits I suggest are all related to dental terminology. | Thank you for this suggestion. We have implemented the recommended changes to terminology, with the exception of “alveolar” bone. For simplicity and based on another reviewer’s recommendation, we now use simply “bone” for consistency with the dental literature.
45 | 7 | Page 1 line 31 change bridgework to fixed dental prosthesis (FDP); jawbone to alveolar bone | See response to comment 44.
46 | 7 | line 42 jawbone to alveolar bone | See response to comment 44.
47 | 7 | line 47 not sure if when you use term bruxism also mean hyper occlusion consider adding hyper occlusion? | See response to comment 44.
48 | 7 | Page 3 line 23 change bridgework to fixed dental prosthesis | See response to comment 44.
49 | 7 | line 26 –32 I found a little confusing and needs clarification it appears to be discussing early loading vs late loading need to get the terminology correct | Thank you. We have clarified this section.
50 | 7 | line 39 jawbone to alvoelar bone | See response to comment 44.
51 | 7 | line 42 consider replacing osseointegration with bone loss continues | See response to comment 44.
52 | 9 | This is an excellent review - and is congruent with our paper (referenced) so I really like it! The obvious next step would be to utilize the VA data warehouse to perform a very large retrospective study - probably comprising thousands of patients who received implants. Frankly, in my opinion, is probably worthy of Merit Review funding. | Thank you for this comment.

### REFERENCES

1 Silva CCG, Dos Santos MS, Monteiro J, de Aguiar Soares Carneiro SC, do Egito Vasconcelos BC. Is there an association between the use of antidepressants and complications involving dental implants? A systematic review and meta-analysis. Int J Oral Maxillofac Surg. 2021;50(1):96–103.32534847
2 Tarfa RA, Melder K, Mady LJ, Eibling D. Is mandibular osteomyelitis a sequela of SSRI-induced dental implant failure? A systematic review & case report. American Journal of Otolaryngology. 2022;43(1):103236.34583289
3 Alsaadi G, Quirynen M, Komárek A, van Steenberghe D. Impact of local and systemic factors on the incidence of oral implant failures, up to abutment connection. Journal of Clinical Periodontology. 2007;34(7):610–617.17433044
4 Alsaadi G, Quirynen M, Michiles K, Teughels W, Komárek A, van Steenberghe D. Impact of local and systemic factors on the incidence of failures up to abutment connection with modified surface oral implants. Journal of Clinical Periodontology. 2008;35(1):51–57.
5 Altay MA, Sindel A, Ozalp O, Does the Intake of Selective Serotonin Reuptake Inhibitors Negatively Affect Dental Implant Osseointegration? A Retrospective Study. Journal of Oral Implantology. 2018;44(4):260–265.29517407
6 Block MS, Christensen BJ, Mercante DE, Chapple AG. What Factors Are Associated With Implant Failure? Journal of Oral & Maxillofacial Surgery. 2021;79(1):91–97.32956618
7 Carr AB, Gonzalez RLV, Jia L, Lohse CM. Relationship between Selective Serotonin Reuptake Inhibitors and Risk of Dental Implant Failure. Journal of Prosthodontics. 2019;28(3):252–257.30637850
8 Chatzopoulos GS, Koidou VP, Lunos S, Wolff LF. Implant and root canal treatment: Survival rates and factors associated with treatment outcome. Journal of Dentistry. 2018;71:61–66.29499242
9 Chrcanovic BR, Kisch J, Albrektsson T, Wennerberg A. Factors Influencing Early Dental Implant Failures. Journal of Dental Research. 2016;95(9):995–1002.27146701
10 Chrcanovic BR, Kisch J, Albrektsson T, Wennerberg A. Is the intake of selective serotonin reuptake inhibitors associated with an increased risk of dental implant failure? International Journal of Oral & Maxillofacial Surgery. 2017;46(6):782–788.28222946
11 Deepa, Mujawar K, Dhillon K, Jadhav P, Das I, Singla YK. Prognostic Implication of Selective Serotonin Reuptake Inhibitors in Osseointegration of Dental Implants: A 5-year Retrospective Study. Journal of Contemporary Dental Practice [Electronic Resource]. 2018;19(7):842–846.
12 Ekfeldt A, Christiansson U, Eriksson T, A retrospective analysis of factors associated with multiple implant failures in maxillae. Clinical Oral Implants Research. 2001;12(5):462–467.11564105
13 Hakam AE, Vila G, Duarte PM, Effects of different antidepressant classes on dental implant failure: A retrospective clinical study. Journal of Periodontology. 2021;92(2):196–204.32725908
14 Wu X, Al-Abedalla K, Rastikerdar E, Selective serotonin reuptake inhibitors and the risk of osseointegrated implant failure: a cohort study. Journal of Dental Research. 2014;93(11):1054–1061.25186831