# Evidence Brief: Staffing Models in Specialty Care

## PREFACE

The VA Evidence Synthesis Program (ESP) was established in 2007 to provide timely and accurate syntheses of targeted health care topics of importance to clinicians, managers, and policymakers as they work to improve the health and health care of Veterans. These reports help:

- Develop clinical policies informed by evidence;
- Implement effective services to improve patient outcomes and to support VA clinical practice guidelines and performance measures; and
- Set the direction for future research to address gaps in clinical knowledge.

The program comprises three ESP Centers across the US and a Coordinating Center located in Portland, Oregon. Center Directors are VA clinicians and recognized leaders in the field of evidence synthesis with close ties to the AHRQ Evidence-based Practice Center Program. The Coordinating Center was created to manage program operations, ensure methodological consistency and quality of products, interface with stakeholders, and address urgent evidence needs. To ensure responsiveness to the needs of decision-makers, the program is governed by a Steering Committee composed of health system leadership and researchers. The program solicits nominations for review topics several times a year via the program website (https://www.hsrd.research.va.gov/publications/esp/TopicNomination.cfm).

The present report was developed in response to a request from the VHA Office of Specialty Care Services (SCS) and Chiefs of Medicine Field Advisory Council. The scope was further developed with input from Operational Partners (below) and the ESP Coordinating Center review team.

## ACKNOWLEDGMENTS

The authors are grateful to Kathryn Vela for literature searching, Payten Sonnen for editorial and citation management support, Devan L. Kansagara, MD for technical expertise and review, and the following individuals for their contributions to this project:

### Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Paul R. Conlin, M.D.
  Chair, Chiefs of Medicine Field Advisory Council
  Chief, Medical Service
  VA Boston Healthcare System
- Ajay Dhawan, M.D.
  Acting Chief Officer
  Specialty Care Services

### Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix E in Supplemental Materials for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.

## EXECUTIVE SUMMARY

#### Background

The Evidence Synthesis Program Coordinating Center is responding to a request from the VHA Office of Specialty Care Services (SCS) and Chiefs of Medicine Field Advisory Council, for an Evidence Brief on staffing models used in outpatient specialty care settings. Findings from this Evidence Brief will be used to inform SCS and the Specialty Care Integrated Clinical Community in their support of field-based specialty care programs.

#### Methods

To identify studies, we searched MEDLINE®, Cochrane Database of Systematic Reviews, Cochrane Central Register of Controlled Trials, and other sources up to October 2021. We used prespecified criteria for study selection, data abstraction, and rating internal validity and strength of the evidence. See the Methods section and our PROSPERO protocol for full details of our methodology.

Key Findings

- The addition of new or use of specific types (ie, advanced practice nurses, nurse case managers) of existing specialty care staff in outpatient specialty care may be related to lower utilization, higher access, improved outcomes, reduced costs, and high patient/provider and staff satisfaction. Our confidence in these findings is low due to limitations in study design (ie, lack of comparison groups), lack of information on patient populations, and lack of statistical analysis.
- It is unclear whether the addition of new clinics to support existing specialty care clinics is associated with improvement in productivity or patient-important outcomes.
- Contextual characteristics could not be directly compared across studies, but high patient, provider, and staff satisfaction were consistently associated with the evaluated staffing models or interventions across specialties.
- Future staffing research could be better directed by a conceptual model of outpatient specialty care. Research should also be more rigorous and be designed to explicitly assess how staffing models/interventions affect productivity and patient-important outcomes.

Staffing models in outpatient specialty care are strategies to match the demand for tasks within a clinic or organization with the supply of appropriate staff, with the goals of minimizing staff shortages by increasing the availability and use of staff expertise, and maximizing work outputs. These strategies could increase productivity and improve patient-important outcomes by ensuring that staff who can complete tasks in a clinic or organization are almost always available. By improving staffing models, managers can ensure that inefficiencies or non-value-added time are minimized in a clinical workflow (eg, patients are not stuck waiting for a specific staff member to complete a task), and that more highly trained clinicians and staff are working to the full extent of their expertise and licensure (eg, providers are not performing tasks that could be done by clerks). In this Evidence Brief, we focus our analysis of staffing models and staffing interventions that add or reorganize staff, in new or existing clinics, rather than examining practices to lower staffing demand (ie, changing patient panel sizes or seeking to treat lower-acuity patients).

In outpatient primary care, many strategies for staffing are influenced by the patient-centered medical home (PCMH) model, which suggests that a primary provider lead a team of non-provider staff to collaboratively care for all the healthcare needs of a panel of patients. In the Veterans Health Administration (VHA), this model is formalized as the patient-aligned care team (PACT), which prescribes a teamlet of 1 provider, 1 registered nurse care manager, 1 licensed practical nurse or medical assistant, and 1 administrative clerk. In outpatient specialty care, staffing models are not as well formalized, but several competing strategies exist (eg, adding new staff vs adding new clinics).

For this Evidence Brief, we sought to synthesize the evidence in the literature on the relationships between staffing models, productivity, and patient-important outcomes in outpatient specialty care. Our second goal was to document the variation in these models and their relationships to outcomes by contextual characteristics (eg, program type or rurality).

Evidence from 8 studies (in 10 publications) suggests that staffing models that add or integrate existing non-physician staff in specialty care outpatient clinics may be associated with lower utilization, higher access, improved outcomes, reduced costs, and high patient/provider and staff satisfaction. However, our confidence in these findings is low due to limitations in study design (ie, lack of a comparison group), methodological limitations within studies, and lack of comparable staffing models or outcome measures across studies. It is unclear whether adding new clinics to support existing specialty care outpatient clinics is associated with improved productivity or patient-important outcomes. Only 2 studies assessed adding new clinics and were limited by lack of information about the study and comparison populations, and lack of analysis. Contextual characteristics of staffing models were not compared within studies directly. We did find that different staffing models or interventions were related to high patient satisfaction and positive provider and staff satisfaction across specialties when these models/interventions were compared indirectly between studies.

Most studies evaluated in this review were of fair or poor quality. Of the 8 studies included, only 2 studies employed either a comparison group or statistical analysis alone. Most studies presented their results as a case study, instead of describing detailed methods and analyses. This lack of detail made it difficult to ascertain the associations between staffing models or interventions, productivity, and patient-important outcomes.

Future research should focus on evaluating the addition of a specific type of non-physician staff member or new clinic across specialties in the VHA. A conceptual model of VHA specialty care would also aid in developing and evaluating new staffing models. Stakeholders should develop such a model to aid in future staffing research. Also, future research should involve more rigorous study designs to assess how staffing models affect productivity and patient-important outcomes (ie, via randomized interventional study designs). Future publications should also include more methodological detail. More rigorous and well-documented staffing research with high quality study designs based on an agreed upon conceptual model could aid in developing more productive and higher quality outpatient specialty care.

## INTRODUCTION

### PURPOSE

The Evidence Synthesis Program (ESP) Coordinating Center is responding to a request from the VHA Office of Specialty Care Services (SCS) and Chiefs of Medicine Field Advisory Council, for an Evidence Brief on staffing models used in outpatient specialty care settings. Findings from this brief will be used to inform SCS and the Specialty Care Integrated Clinical Community in their support of field-based specialty care programs.

### BACKGROUND

Staffing models are strategies to match the demand of tasks in an organization with the supply of staff, with the goals of minimizing staffing shortages, increasing the availability and use of staff expertise, and maximizing work outputs.^1^ Tasks that are nonrepetitive in nature can be challenging to effectively staff; in healthcare settings in particular, nonrepetitive and complex tasks are prevalent and often reach across staff specializations. A common solution to addressing this challenge is the creation of healthcare teams.^2^ Although teamwork in healthcare settings is associated with better staff performance (eg, improved processes or outcomes),^3^ research on and use of staffing models has generally been limited to inpatient and primary care settings. For example, a previous Cochrane review examined the relationships between inpatient nursing staffing levels/models and patient-important outcomes, but only found that staffing advanced or specialist nurses was not related to patient mortality.^4^

In primary care, the dominant staffing model is based in the patient-centered medical home (PCMH) care model. In PCMH, patients have a personal relationship with a primary care physician (PCP) who is responsible for all patient healthcare needs and for coordinating care across specialties.^5^ PCPs lead a team of, on average, 4 non-provider staff to collaboratively care for a panel of patients; non-provider staff can include nurse care managers, pharmacists, and nutritionists.^6^ In the VHA, the PCMH model was adapted into the patient-aligned care team (PACT),^7^ where a provider and 3 additional non-provider staff (1 registered nurse care manager, 1 licensed practical nurse or medical assistant, and 1 administrative clerk) are organized into a teamlet. As shown in Figure 1, the PACT is conceptually supported by 3 pillars: access, care management and coordination, and practice redesign; these elements are further supported by patient-centeredness, [system] improvement, and resources.^8^ The goals of each pillar are to increase appointment availability and non-appointment options (access), ensure that high-risk transitions are well-managed (care management and coordination), and to improve communication and work processes (practice redesign).

Figure 1 PACT Conceptual Model

Note. Figure adapted from Bidassie et al.^8^

A meta-analysis of 19 PCMH interventions found that the model had small-to-moderate positive effects on the delivery of preventive care and a small positive effect on patient experience, with moderate strength of evidence.^9^ The review also found low strength of evidence for a small-to-moderate positive effect of PCMH on staff experience, and reduced emergency department visits. In the VHA, a nationwide observational study of 913 clinics, 5404 primary care staff, and 5.6 million Veterans found that clinics with better PACT implementation (ie, clinics that best adhere to the optimal PACT model) were associated with higher patient satisfaction, higher performance on clinical quality measures, lower staff burnout, and lower hospitalization and emergency department use.^10^ A rapid review of different team-based primary care structures found moderate strength of evidence for a nurse chronic care manager on improved patient outcomes, and low strength of evidence for nurse practitioner team co-managers on increased patient access, retrained medical assistants on increased screening rates, and variable team staff professions to match patient populations on higher quality of care.^11^

Use of staffing models in outpatient specialty care settings may have similar benefits to productivity and patient-important outcomes by better matching staff to tasks appropriate for their skillsets, and by ensuring that staff are most efficiently utilized to avoid shortages. As in primary care, these models could make use of new or existing non-provider staff to complete different tasks or could be used to create new clinics to reorganize how all providers and staff collectively complete tasks to deliver patient care. No single staffing model is dominant in outpatient specialty care, but it is possible that similar models could be effective across specialties. In Table 1, we present possible outpatient specialty care staffing models or interventions, organized after the abovementioned Cochrane review^4^ on inpatient staffing models.

Table 1 Example Staffing Models/Interventions in Healthcare

Type | Description
New Staff | Adding new staff members; Example: addition of a nurse case manager to optimize patient management and care
Different Use of Staff | Changing staff duties to increase efficiency; Example: specialist nurse now engages in regular patient follow-up visits instead of a specialist physician
New Clinic | Adding a new clinic or integrating new functions into an existing clinic to meet a specific clinic need; Example: addition of a new clinic to treat specific symptoms or triage patients into different types of care
New Teamwork | Implementing new teams of staff to optimize staff and resource utilization; Example: creating a specific team of clinicians and staff to meet clinic needs
Improved Teamwork | Reorganizing staff to increase efficiency; Example: assigning staff specific roles in a clinic to improve their workflow
Change in Working Hours | Shifting or increasing/decreasing working hours for some or all staff to meet patient demand; Example: opening a night clinic for several nights a week so that patients can see their specialty provider after normal business hours
Change in Staffing-Related Clinic Resources | Adding or removing clinic resources to help staff maximize their productivity; Example: adding additional exam rooms to a clinic so that lack of space is no longer an impediment to staff workflow

In summary, PCMH and PACT staffing models in primary care have been associated with increases in quality, access, patient and staff experience, and with fewer hospital admissions and emergency department visits. Compared with inpatient and primary care staffing models, however, the effects of different staffing models in outpatient specialty care are not well understood. The aim of this report is to summarize the literature on the relationships between outpatient specialty care staffing models, staff productivity, and patient-important outcomes, and describe how these models vary by program and contextual characteristics. In this Brief, we focus on supply-side changes to staffing (ie, new or different staff or clinics), rather than demand-side changes (ie, fewer or less complex patients).

## METHODS

### PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42021285060).

### KEY QUESTIONS

The following key questions were the focus of this review:

Key Question 1 What staffing models for outpatient specialty care clinical support staff and clinicians are associated with increased staff productivity and improved patient outcomes?
Key Question 2 How do staffing models for outpatient specialty care clinical support staff and clinicians vary by program or contextual characteristics (eg, program type, rural or urban setting, etc)?

### ELIGIBILITY CRITERIA

The ESP included studies that met the following criteria:

Population | Outpatient specialty care programs (allergy/immunology, cardiology, critical care/pulmonary, dermatology, endocrinology/diabetes, gastroenterology, HIV/hepatitis, infectious disease, nephrology, neurology, oncology, optometry, pain management, rheumatology, sleep medicine)
Intervention | Staffing models (ie, practices for adding/removing staff, expanding or reducing work hours, or altering allocation of clinic resources [eg, clinic room availability]) for outpatient specialty care program clinical support staff and clinicians (excluding administrative staff)
Comparator | Alternative staffing models (ie, implemented in comparable setting), pre/post implementation of staffing model, or no comparator
Outcomes | - Productivity outcomes (healthcare utilization [ie, reduction in emergency department visits, number of patients seen], provider and staff satisfaction, cost-effectiveness), quality [ie, meeting a quality measure]); - Patient-important outcomes (patient satisfaction, healthcare access [eg, wait times for appointments], equity [eg, disparities in care], patient health outcomes [eg, HIV viral suppression])
Timing | Any
Setting | United States
Study Design | Any, but we may prioritize articles using a best-evidence approach to accommodate Evidence Brief timeline

### DATA SOURCES AND SEARCHES

To identify articles relevant to the key questions, a research librarian searched Ovid MEDLINE, CINAHL, Cochrane Database of Systematic Reviews, and ClinicalTrials.gov as well as AHRQ and HSR&D databases through October 2021 using terms for outpatient specialty care programs (ie, immunology, oncology, cardiology), staffing and workload (see Appendix A in Supplemental Materials for complete search strategies). Additional citations were identified from hand-searching reference lists and consultation with content experts. We limited the search to published and indexed articles involving human subjects available in the English language. Study selection was based on the eligibility criteria described above. Models involving medical scribes were excluded, as a recent ESP systematic review^12^ covered this intervention type in cardiology, orthopedic, and emergency departments. Titles, abstracts, and full-text articles were reviewed by 2 investigators. All disagreements were resolved by consensus or discussion with a third reviewer.

### DATA ABSTRACTION AND ASSESSMENT

Effect information and population, intervention (or staffing model, if study involved no intervention), and comparator characteristics were abstracted from all included studies. The internal validity (risk of bias) of each included study was rated using the Cochrane Risk of Bias tools for randomized controlled trials^13^ and unrandomized studies,^14^ as well as the Joanna Briggs Institute (JBI) Checklist for cross-sectional and repeated cross-sectional studies.^15^ All data abstraction and internal validity ratings were first completed by 1 reviewer and then checked by another; disagreements were resolved by consensus or discussion with a third reviewer.

We graded the strength of the evidence (SOE) for each outcome based on the AHRQ Methods Guide for Comparative Effectiveness Reviews.^16^ This approach provides a rating of confidence in reported findings based on trial methodology (design, quality, and risk of bias), consistency (whether effects are in the same direction and have a consistent magnitude), and directness (whether assessed outcomes are clinically important to patients and providers). When information on precision of findings (eg, confidence intervals) is available, certainty of evidence is also evaluated. Because of substantial variation in outcomes across studies, we assessed strength of evidence for each intervention type/model rather than for each outcome type. For this review, high strength evidence consisted of multiple, large trials with low risk of bias (or good quality) and consistent and precise findings. Moderate strength evidence consisted of multiple trials with low or unclear risk of bias (mostly good or fair quality), and consistent and precise findings. Low strength evidence consisted of a single study or multiple small studies with unclear, some concerns for, or high risk of bias (or mostly fair or poor study quality) and inconsistent or imprecise findings. Insufficient evidence consisted of a single study or multiple small studies with unclear, some concerns for, or high risk of bias (or mostly fair or poor study quality) and inconsistent interventions/models and/or outcomes.

### SYNTHESIS

We synthesized available evidence narratively by staffing model type (addition of new staff or redefined roles of existing staff, or establishment of a new clinic), describing patient and staffing characteristics and outcomes.

## RESULTS

### LITERATURE FLOW

The literature flow diagram (Figure 2) summarizes the results of the study selection process (full list of excluded studies available in Appendix B in Supplemental Materials).

Figure 2 Literature Flowchart

Abbreviation. CINAHL=Cumulative Index of Nursing and Allied Health.

### LITERATURE OVERVIEW

Our search identified 5,068 potentially relevant articles. We included 8 studies in 10 publications,^17–26^ which are summarized in Table 2 (see Appendix C in Supplemental Materials for full study details). Most studies^17,20,22,24–26^ examined the impact of new or additional mid-level staff or advanced practice providers (ie, nurses, advanced practice nurses [APNs], nurse practitioners [NPs], or physician assistants [PAs]) on productivity (ie, number of patients seen, ED visits or hospitalizations, or staff satisfaction) or patient outcomes (ie, patient satisfaction or symptom management). Two studies^21,23^ examined the impact of new clinics developed to meet a specific clinical need (eg, symptom management among patients with breast cancer). Among the 5 studies reporting patient sample size, the median sample size was 199 (range: 55-15,381), with all but 2 studies including fewer than 200 patients. We identified 1 study in progress (see Appendix D in Supplemental Materials), which examined the use of a specially trained aid to support outpatient care for patients with congestive heart failure.

We excluded 51 studies after full-text screening for examining an ineligible intervention. Most of these studies evaluated interventions that were completely unrelated to staffing or work, but we did exclude a few intervention categories that were close to our topic but did not meet our inclusion criteria. These ineligible intervention categories included: telemedicine or telehealth interventions, descriptions of staffing interventions that did not include an evaluation, non-intervention measures of staffing, and non-staffing resource interventions (eg, changing patient registration procedures). We also excluded 32 studies for containing ineligible outcomes. Several of these studies did describe a staffing model or intervention but reported no eligible quantitative outcomes. The full list of excluded studies is available in Appendix B.

Of the studies that met inclusion criteria, most were cross-sectional^17,20,25^ or repeated cross-sectional design.^21,24,26^ Common limitations among the cross-sectional studies included lack of information on the patient population and lack of statistical analysis. Two cohort studies^22,23^ were limited by lack of data provided on the samples, making it difficult to assess whether observed outcome changes were more likely due to the intervention or other sample characteristics.

No evidence was rated as high or moderate strength due to variability in staffing models and outcome measurement and study design limitations (eg, lack of comparison groups and/or statistical analysis). Our overall confidence in the evidence is low or insufficient due to limitations in study design (eg, lack of comparison group), other methodological limitations of the studies, and inconsistency in staffing models and outcome measurement. Additionally, lack of methodological detail made it difficult to evaluate reported associations between staffing models, productivity, and patient-important outcomes.

Table 2 Characteristics of Included Studies

Author, Year | Study Design | Sample Size; Follow-up | Specialty Area | Population | Staffing Characteristics | Productivity Outcomes^a^ | Patient-Important Outcomes^b^
New or Existing Staff
Albert 2010^17^ | Cross-sectional | N=15,381 patients in 167 practices; NA | Cardiology | Patients with chronic HF or previous MI | Number of APNs or PAs/ practice | None | Compliance with guideline-recommended therapy
Garnett 2020^20^ | Cross-sectional | N=1,790 patients in 1 practice (12 NCMs); NA | Hematology | Adult patients with complex hematologic cancer | Existence of NCMs | ED visits; Hospital admission or readmission | Patient self-management; Patient treatment adherence; Change in health behavior; Improved continuity of care
Huang 2018^22^ | Uncontrolled Pre/post | N=55 patients in 1 practice; 5 weeks/1.33 months [40 days] | Hematology/oncology | Patients in an outpatient chemotherapy unit | Schedule optimization to reduce staffing violations of nurse-to-patient ratios | Patient volume; Average chair utilization; Provider and staff satisfaction; Resource constraint violations | Patients wait time to treatment initiation; Wait time between provider visit and infusion
Ross 2014^24^ | Repeated cross-sectional | NR; 32 weeks/8 months | Neurology | Patients referred for new neurologic symptoms | A new clinical team to evaluate patients with new neurologic symptoms or signs and provide direction for patients to: primary care physician, a subspecialty clinic, or a general neurology physician who provides ongoing care | Lead time (time to 3^rd^ available appointment) | Patient satisfaction
Ruder 2011^25^ | Cross-sectional | N=199 patients in 1 practice; NA | Oncology | Ambulatory oncology clinic patients: Diagnoses included solid tumors (89%), hematological malignancies (3%), and miscellaneous diseases (8%) | Addition of an oncology pharmacist to an outpatient oncology clinic to provide patient and family education, medication history and reconciliation, adverse drug event monitoring, symptom management, and chemotherapy regimen review | Number of patients seen by pharmacist; Number of pharmacist clinical interventions; Number of pharmacist consultation interventions; Colleague satisfaction; Cost | Patient satisfaction; Adverse events;
Smith 2004^26^ | Repeated cross-sectional | NR; NA | Nephrology | Huntsville Medical Group’s rural ESRD patients on chronic dialysis | Advanced practice providers (PAs, NPs) integrated into the Huntsville Medical Consulting Group practice in a rural dialysis clinic to visit chronic dialysis patients 1x per week to review medications, treatment plans, and vascular access | Hospital admission; Number of inpatient days; Length of hospital stay | Mortality
New Clinic
Graze 2014^21^ | Repeated cross-sectional | NR; 72 weeks/18 months | Oncology | Breast cancer patients attending the Anne Arundel Medical Center DeCesris Cancer Institute | Symptom management clinic (SMC) led by advanced oncology NPs, embedded within oncology practice at medical center. Existing oncology nurse triage call system was integrated with the SMC to enhance coordination, communication, and patient education | Oncology unit admissions; ED visits; Breast Cancer Care Quality Measures set | Patient satisfaction
Reese 2021^23^ | Retrospective cohort study | N=133 patients in 1 practice; NA | Neurology | Patients presenting to outpatient neurology clinic deemed appropriate candidates for headache infusion by clinic nurse | Headache Infusion Center set up infusion patients following a multistep protocol to meet neurology team’s clinical experience and patient needs | Duration of visit; Cost | Patient satisfaction; Pain relief

Notes.

a Productivity outcomes include: Utilization (ie, number of visits, emergency department visits), cost, and provider and staff satisfaction, and quality (ie, meeting a quality measure);

b Patient-important outcomes include patient satisfaction, healthcare access (eg, wait times for appointments), equity (eg, disparities in care), patient health outcomes (eg, symptom improvement).

Abbreviations. APN=advanced practice nurse; HF=heart failure; MI=myocardial infarction; NA=not available; NCM=nurse care manager; NP=nurse practitioner, NR=not reported; PA=physician’s assistant.

### EFFECTIVENESS OF STAFFING MODELS FOR OUTPATIENT SPECIALTY CARE

#### New or Existing Staff

Three studies^24–26^ that examined adding new staff to outpatient specialty clinics reported high patient, provider, and staff satisfaction and reductions in appointment wait times, inpatient admissions, and mortality (Table 3). In 1 study,^24^ a new clinical team (1 physician, 2 NPs, 1 PA, supporting nursing, and medical staff) added to an outpatient neurology clinic to evaluate new neurology referrals and direct them either to primary care, a subspecialty clinic, or a general neurology physician, reduced monthly lead time (defined as time to third available appointment) from 299 days pre-implementation to 10 days post-implementation. Patient satisfaction was unchanged, with the same mean score pre- and post-implementation. In another study,^26^ the addition of a physician extender (ie, NP or PA) to provide weekly visits, medication review, symptom management, and outreach reduced inpatient admissions, number of inpatient days, and mortality among outpatient chronic dialysis clinic patients. One study in an outpatient oncology setting^25^ reported high levels of patient, provider, and staff satisfaction with the addition of an oncology pharmacist providing patient education, medication reconciliation, adverse drug event monitoring, and symptom management. Our confidence in these findings is low as they come from cross-sectional or repeated cross-sectional studies with limited information on the study samples and limited or no analysis of data.

Among studies examining existing staff (Table 4), 1 study^17^ assessed compliance to guideline-recommended heart failure measures among 167 outpatient cardiology practices based on the number of APNs or PAs on staff (0 vs >0 to <2 vs ≥2) and reported that practices with at least 2 APNs or PAs had greater compliance with 2 out of the 7 assessed measures compared to practices with less than 2 APNs or PAs; no significant differences were observed between practices in the other 5 measures. Another study^22^ reported reduced staffing violations after implementing a scheduling optimization intervention in an outpatient chemotherapy unit, and a final included study^20^ linked nurse case manager activities to various quality measures, including improved continuity of care, patient self-management, and treatment adherence among complex hematologic cancer patients. As with studies of added staff, our confidence in these findings is low as they come from mostly cross-sectional or repeated cross-sectional studies with limited information on the study samples and limited or no analysis of data.

Table 3 Outcomes of Adding New Staff to an Existing Model of Care

Author, Year; N | Specialty Area | Staffing Intervention/Model | Productivity Outcomes | Patient-Important Outcomes
Ross 2014^24^; NR | Neurology | New clinical team (1 physician, 2 NPs, 1 PA) to evaluate and direct new neurology referrals | [underlined: Utilization]; Monthly Lead Time:^a^ 299 days pre- vs 10 days post-implementation | [underlined: Patient Satisfaction]; Mean score (out of 100) 89.25 pre- vs 89.25 post-implementation
Ruder 2011^25^; N=199 | Oncology | Oncology pharmacists providing patient education, medication reconciliation, and symptom management | [underlined: Utilization]; Average of 2.9 visits with pharmacist per patient during treatment; 583 pharmacist clinical interventions; [underlined: Cost] ^b^; Saved $210,000 in chemotherapy costs; [underlined: Provider and Staff Satisfaction]; 98% positive ratings | [underlined: Patient Satisfaction]; 95% positive ratings
Smith 2004^26^; NR | Nephrology | Advanced practice providers (NP or PA) providing weekly visits, medication and treatment review, and outreach | [underlined: Utilization]; Hospital admission frequency: 1.75 pre- vs 1.27 post-implementation; Inpatient days/dialysis patient: 14.25 pre- vs 7.3 post-implementation | [underlined: Patient Health]; Mortality: 19.01% pre- vs 9.3% post-implementation

Notes.

a Defined as time to 3^rd^ available appointment;

b Estimated from reduced chemotherapy mixing and reduced dosages.

Abbreviations. NP=nurse practitioner; NR=not reported; PA=physician assistant.

Table 4 Outcomes of Existing Staff on an Existing Model of Care

Author, Year; N | Specialty Area | Staffing Intervention/Model | Productivity Outcomes | Patient-Important Outcomes
Albert 2010^17^ | Cardiology | Number of existing APNs or PAs on staff | [underlined: Quality]; Conformity to guideline-recommended HF measures: ≥ 2 APNs or PAs greater conformity (vs <2 APNs or PAs) for implantable cardioverter-defibrillator therapy and delivery of HF education, p<0.01 for both (NSD other measures) | NR
Garnett 2020^20^ | Oncology/Hematology | Nurse case manager activities | [underlined: Utilization] ^a^; Prevention of ED visits: 1%; Prevention of admission or readmission to hospital: 1%; [underlined: Quality] ^a^; Improved continuity of care: 52% | [underlined: Patient Health] ^a^; Patient self-management: 15%; Patient treatment adherence: 7%; Change in health behavior: 21%
Huang 2018^22^ | Oncology | Scheduling optimization | [underlined: Utilization] (pre- vs post-implementation); Patient volume: 44.7 vs 44.7; Average chair utilization: 8.8 vs 8.3; Resource constraint violation: 20.1 vs 14.7; [underlined: Provider and Staff Satisfaction]; Overall feedback from managers, physicians, nurses, pharmacists, and nurses was positive (data NR) | [underlined: Healthcare Access]; Patient wait time to treatment initiation decreased from as much as 40 minutes to 5 minutes (data NR); Wait time between provider visit and infusion appointment: 5 to 15-minute increase (data NR)

Notes.

a Percentage of occurrences of quality measures that were linked to nurse case manager activities.

Abbreviations. APN = advanced practice nurse; NCM = nurse case manager; NR = not reported; NSD = no significant difference; PA = physician assistant; RN = registered nurse.

#### New Clinics

Two studies^21,23^ examined the effect of developing new clinics to meet specific needs within established outpatient clinics (Table 5).^21,23^ In an outpatient oncology clinic, integrating a symptom management clinic led by oncology APNs into an existing oncology nurse triage system with the goal of enhancing coordination, communication, and patient education reduced oncology inpatient admissions and increased patient satisfaction scores. In another study,^23^ a new headache infusion center staffed by RNs was able to reduce visit duration and cost by accommodating patients presenting to an outpatient neurology clinic meeting eligibility criteria for headache infusion with high patient satisfaction. However, we found these studies to provide insufficient evidence as they were limited by lack of information about the study and comparison populations, and lack of analysis.

Table 5 New Clinics Established Within an Existing Outpatient Setting

Author, Year; N | Specialty Area | Staffing Intervention/Model | Productivity Outcomes | Patient-Important Outcomes
Graze 2014^21^; NR | Oncology | Symptom management clinic integrated into nurse triage call system | [underlined: Utilization]; Oncology unit admissions: 26 per month pre- vs 17 per month post-integration; ED Visits: At least 40 ED visits prevented (data NR) | [underlined: Patient Satisfaction]; 80% pre- vs 90% post-integration^a^
Reese 2021^23^; N=133 | Neurology | Headache infusion center added to outpatient neurology center | [underlined: Utilization]; Duration of visit (mean) 2.51 hrs. infusion clinic vs 6.24 hrs ED^b^; [underlined: Cost]; Mean cost of visit $962 infusion clinic vs $10,375 ED | [underlined: Patient Satisfaction]; Mean score (out of 5) 4.2 to 4.96 on all measures

Notes.

a Percentages estimated from Figure 2 in Graze 2014;

b Compared to patients with “comparable issues” seen in the ED.

Abbreviations. ED = emergency department; Hrs = hours; NR = not reported.

### STAFFING MODEL CONTEXTUAL CHARACTERISTICS

We did not identify any studies that compared different staffing models head-to-head, so we cannot make any direct conclusions about the relationship between staffing models and contextual characteristics (eg, specialty, rurality, adding staff vs clinics, etc). Studies did vary by specialty and rurality, but indirect comparisons of these characteristics across studies also could not be made for most outcomes, as they were not consistent between studies. However, patient, provider, and staff satisfaction were high or positive across studies of different specialties. Patient satisfaction was frequently measured (4 studies),^21,23–25^ and was consistently high. Provider and staff satisfaction, measured in 2 studies,^22,25^ was high in 1 study, and positive but not quantitatively reported in the other.

## DISCUSSION

Staffing interventions/models that add or integrate existing non-physician staff in specialty care outpatient clinics may be linked to lower utilization, higher access, improved outcomes, reduced costs, and high patient/provider and staff satisfaction. Our confidence in these findings is low, as most are derived from studies using a cross-sectional, repeated cross-sectional, or uncontrolled pre-post study design, without a comparison group. It is unclear whether adding new clinics to support existing specialty care outpatient clinics is associated with improved productivity or patient-important outcomes. The 2 identified studies assessing the addition of new clinics were limited by lack of comparison groups and methodological detail. Direct comparisons between intervention types (eg, staff vs clinic interventions), interventions in different specialties, and interventions in urban versus rural areas were not found. Across studies of different specialties, patient, provider, and staff satisfaction were positive or high.

Interventions/models identified in this review either directed patients to an advanced practice provider or staff member rather than a specialist for some of their care or set up a specialty clinic intended to triage patients in some way. Theoretically, both types of interventions/models could improve productivity and patient outcomes, but the evidence is of limited quality to draw any firm conclusions on the topic. Moreover, interventions or models were generally ad hoc in nature, designed specifically for each specialty or even for each clinic. A model of optimal outpatient specialty care like PCMH or PACT in primary care would help in developing and evaluating new staffing models. More directed, focused research on well-defined staffing models in outpatient specialty care is needed.

### LIMITATIONS

The studies found in this review were mostly of fair or poor quality, with only 1 employing a design that utilized a comparison group.^23^ Without a comparison group, it was not possible to determine if the evaluated staffing models perform better than usual care. Further, only 1^17^ of the 8 included studies^17,20–26^ employed any type of statistical analysis. Such analyses may or may not have shown intervention effects, but without them, the strength of evidence is much lower. Studies without statistical analyses presented interventions and findings in a case study fashion that omitted many important details (eg, patient or staff characteristics), as noted in the study quality ratings (see Appendix C in the Supplemental Materials).

### FUTURE RESEARCH

There is need for research on outpatient specialty care staffing in the VHA to examine the addition of a specific type of staff member or clinic across specialties. At present, the existing literature lacks a uniform model of outpatient specialty care staffing. It is unclear if this is due to different specialty needs or a paucity of research on staffing models. Research that focuses on analyzing the effects of advanced practice providers/clinical support staff or triage clinics on productivity and patient outcomes in specialty care could help the VHA optimize its staffing models. Stakeholders in VA should first define a conceptual model of specialty care delivery, like PACT in primary care, and then map ideal staffing and clinics to that model; researchers can then follow this conceptual model as a map to evaluate different staffing or clinic models to determine the best way to deliver specialty care. Without an overarching conceptual model, it would be difficult to direct future work in this area.

In addition, although case studies can be useful for management and practitioners, their findings are difficult to generalize. More rigorous staffing research, including studies with randomized interventional designs (such as the randomized evaluation model used by the VA’s Partnered Evidence-based Policy Resource Center), relevant comparators, and guidance by a specialty care conceptual model, may aid the VHA in identifying effective outpatient specialty care staffing models. In addition, the COVID-19 pandemic, and the ensuing healthcare staffing shortages and shift towards telemedicine, has created new challenges for specialty care staffing. Future research should examine how changes to staffing models can respond to short-term staffing shortages or the need to maintain both in-person and virtual clinics. Even as the pandemic recedes, planning for responsive staffing models should be ongoing to ensure preparedness for future care disruptions.

Finally, many VA facilities and clinics, like other major healthcare systems with teaching hospitals, utilize healthcare trainees (including physician residents and fellows) to assist in providing patient care while receiving training. Research should examine how these trainees can augment existing specialty care staffing levels, while still maintaining quality of care and maximizing trainee education.

### CONCLUSIONS

Little evidence is available on staffing models in the outpatient specialty care context. Existing models are generally ad hoc in nature, and research to date has lacked an overarching conceptual model analogous to those used in primary care settings and has been hampered by methodological inconsistency and other limitations. In the VA context, development and implementation of specialty care staffing models that improve productivity and patient outcomes would be facilitated through use of 1) an overarching conceptual framework that identifies key staffing model elements and outcomes across specialty care settings, and 2) more rigorous study designs and analysis methods that would increase the informativeness of evidence on specialty care staffing models

## REFERENCES

1 NASEM. Facilities Staffing Requirements for the Veterans Health Administration Resource Planning and Methodology for the Future. Washington, DC 2020.
2 Rosen MA, DiazGranados D, Dietz AS, . Teamwork in healthcare: Key discoveries enabling safer, high-quality care. Am Psychol. 2018;73(4):433–450.29792459
3 Schmutz JB, Meier LL, Manser T. How effective is teamwork really? The relationship between teamwork and performance in healthcare teams: a systematic review and meta-analysis. BMJ Open. 2019;9(9):e028280.
4 Butler M ST, Halligan P, Sheridan A, Kinsman L, Rotter T, Beaumier J, Kelly RG, Drennan J. Hospital nurse-staffing models and patient- and staff-related outcomes. Cochrane Database of Systematic Reviews. 2019(4).
5 American Academy of Family Physicians. Joint Principles of the Patient-Centered Medical Home. 2007. https://www.aafp.org/dam/AAFP/documents/practice_management/pcmh/initiatives/PCMHJoint.pdf.
6 Mitesh S. Patel MM, Martin J. Arron MM, Thomas A. Sinsky MD, . Estimating the Staffing Infrastructure for a Patient-Centered Medical Home. The American Journal of Managed Care. 2013;19(6).
7 Rosland AM, Nelson K, Sun H, . The patient-centered medical home in the Veterans Health Administration. Am J Manag Care. 2013;19(7):e263–272.23919446
8 Bidassie B, Davies ML, Stark R, Boushon B. VA experience in implementing Patient-Centered Medical Home using a breakthrough series collaborative. Journal of general internal medicine. 2014;29 Suppl 2(Suppl 2):S563–S571.24715402
9 Jackson GL, Powers BJ, Chatterjee R, . The patient centered medical home. A systematic review. Ann Intern Med. 2013;158(3):169–178.24779044
10 Nelson KM, Helfrich C, Sun H, . Implementation of the patient-centered medical home in the Veterans Health Administration: associations with patient satisfaction, quality of care, staff burnout, and hospital and emergency department use. JAMA Intern Med. 2014;174(8):1350–1358.25055197
11 Shekelle PG BM. What are the Effects of Different Team-Based Primary Care Structures on the Quadruple Aim of Care?: A Rapid Review. Washington, DC: Evidence Synthesis Program, Health Services Research and Development Service, Office of Research and Development, Department of Veterans Affairs VA ESP Project #05-226 2021.
12 Ullman K ML, Bart B, Park G, MacDonald R, Linskens E, Wilt TJ. The effect of medical scribes in cardiology, orthopedic, and emergency departments: a systematic review. Washington, DC: Evidence Synthesis Program, Health Services Research and Development Service, Office of Research and Development, Department of Veterans Affairs VA ESP Project #09-009 2020.
13 Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. 2019;366:l4898.31462531
14 Thomson H, Craig P, Hilton-Boon M, Campbell M, Katikireddi SV. Applying the ROBINS-I tool to natural experiments: an example from public health. Systematic Reviews. 2018;7(1):15.29368630
15 Joanna Briggs Institute. Critical Appraisal Tools. Joanna Briggs Institute (JBI). https://jbi.global/critical-appraisal-tools. Accessed Dec., 2021.
16 Berkman ND, Lohr KN, Ansari MT, . Grading the strength of a body of evidence when assessing health care interventions: an EPC update. In. Journal of clinical epidemiology. Vol 682015:1312–1324.
17 Albert NM, Fonarow GC, Yancy CW, . Outpatient cardiology practices with advanced practice nurses and physician assistants provide similar delivery of recommended therapies (findings from IMPROVE HF). American Journal of Cardiology. 2010;105(12):1773–1779.
18 Fessele K, Yendro S, Mallory G. Setting the bar: developing quality measures and education programs to define evidence-based, patient-centered, high-quality care. Clinical Journal of Oncology Nursing. 2014;18.
19 Fonarow GC, Albert NM, Curtis AB, . Improving evidence-based care for heart failure in outpatient cardiology practices: primary results of the Registry to Improve the Use of Evidence-Based Heart Failure Therapies in the Outpatient Setting (IMPROVE HF). In. Circulation. Vol 1222010:585–596.
20 Garnett D, Hardy L, Fitzgerald E, Fisher T, Graham L, Overcash J. Nurse Case Manager: Measurement of Care Coordination Activities and Quality and Resource Use Outcomes When Caring for the Complex Patient With Hematologic Cancer. Clinical Journal of Oncology Nursing. 2020;24(1):65–74.31961839
21 Graze L, Brady-Copertino C, Varner A, Stiver WS. The development of a nursing assessment and symptom management clinic. Clinical Journal of Oncology Nursing. 2014;18 Suppl:12–16.25252985
22 Huang YL, Bryce AH, Culbertson T, . Alternative Outpatient Chemotherapy Scheduling Method to Improve Patient Service Quality and Nurse Satisfaction. Journal of oncology practice/American Society of Clinical Oncology. 2018;14(2):e82–e91.
23 Reese O, Wright C, Sandoval A, . “Establishment of an acute headache infusion clinic as an alternative for emergency department care”. Journal of the Neurological Sciences. 2021;423:117384.33714085
24 Ross SC. An option for improving access to outpatient general neurology. Neurology Clinical Practice. 2014;4(5):435–440.29443242
25 Ruder AD, Smith DL, Madsen MT, Kass FH, 3rd. Is there a benefit to having a clinical oncology pharmacist on staff at a community oncology clinic? Journal of Oncology Pharmacy Practice. 2011;17(4):425–432.21248174
26 Smith GO, Jr. The role of physician assistants in improving renal care. Nephrology News & Issues. 2004;18(5):51–56.

## Supplemental Materials

### APPENDIX A SEARCH STRATEGY

#### SYSTEMATIC REVIEWS

Search for current systematic reviews (limited to last 7 years); Date Searched: 10-15-21
A. Bibliographic Databases: | # | Search Statement | Results
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to October 14, 2021 | [underlined: 1] | (Outpatients/ AND (“Allergy and Immunology”/ OR Cardiology/ OR Critical Care/ OR Respiratory Therapy/ OR Dermatology/ OR exp Diabetes Mellitus/ OR Gastroenterology/ OR HIV/ OR Hepatitis B/ OR Hepatitis C/ OR Infectious Disease Medicine/ OR Nephrology/ OR Neurology/ OR exp Medical Oncology/ OR Optometry/ OR Pain Management/ OR Rheumatology/ OR Sleep Medicine Specialty/)) OR (((Outpatient$1 OR (outpatient adj3 (care OR clinic$1))) AND (vascular medicine OR cardiology OR angiology OR cardiovascular disease OR dermatology OR critical care OR ICU OR intensive care OR endocrinology OR gastroenterology OR sleep medicine OR hepatology OR infectious disease$1 OR nephrology OR neurology OR nervous system OR oncology OR cancer OR optometry OR rheumatology OR immunology OR allergy OR HIV OR AIDS OR hepatitis OR diabetes OR pulmonary OR respiratory therap*))).ti,ab. | 48686
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to October 14, 2021 | [underlined: 2] | Personnel Staffing and Scheduling/ OR Shift Work Schedule/ OR Work Schedule Tolerance/ OR Workload/ OR Workforce/ OR Models, Nursing/ OR Resource Allocation/ OR (schedule* OR staff* OR personnel OR workload$1 OR work hours OR work load$1 OR nursing model$1 OR staffing model$1 OR (resource adj1 allocation) OR resource$1).ti,ab. | 871713
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to October 14, 2021 | [underlined: 3] | 1 AND 2 | 5310
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to October 14, 2021 | [underlined: 4] | [underlined: (systematic review.ti. or meta-analysis.pt. or meta-analysis.ti. or systematic literature review.ti. or this systematic review.tw. or pooling project.tw. or (systematic review.ti,ab. and review.pt.) or meta synthesis.ti. or meta-analy*.ti. or integrative review.tw. or integrative research review.tw. or rapid review.tw. or umbrella review.tw. or consensus development conference.pt. or practice guideline.pt. or drug class reviews.ti. or cochrane database syst rev.jn. or acp journal club.jn. or health technol assess.jn. or evid rep technol assess summ.jn. or jbi database system rev implement rep.jn. or (clinical guideline and management).tw. or ((evidence based.ti. or evidence-based medicine/ or best practice*.ti. or evidence synthesis.ti,ab.) and (((review.pt. or diseases category/ or behavior.mp.) and behavior mechanisms/) or therapeutics/ or evaluation studies.pt. or validation studies.pt. or guideline.pt. or pmcbook.mp.)) or (((systematic or systematically).tw. or critical.ti,ab. or study selection.tw. or ((predetermined or inclusion) and criteri*).tw. or exclusion criteri*.tw. or main outcome measures.tw. or standard of care.tw. or standards of care.tw.) and ((survey or surveys).ti,ab. or overview*.tw. or review.ti,ab. or reviews.ti,ab. or search*.tw. or handsearch.tw. or analysis.ti. or critique.ti,ab. or appraisal.tw. or (reduction.tw. and (risk/ or risk.tw.) and (death or recurrence).mp.)) and ((literature or articles or publications or publication or bibliography or bibliographies or published).ti,ab. or pooled data.tw. or unpublished.tw. or citation.tw. or citations.tw. or database.ti,ab. or internet.ti,ab. or textbooks.ti,ab. or references.tw. or scales.tw. or papers.tw. or datasets.tw. or trials.ti,ab. or meta-analy*.tw. or (clinical and studies).ti,ab. or treatment outcome/ or treatment outcome.tw. or pmcbook.mp.))) not (letter or newspaper article).pt.] | [underlined: 479631]
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to October 14, 2021 | [underlined: 5] | [underlined: 7 and 8] | [underlined: 177]
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL 1946 to October 14, 2021 | [underlined: 6] | [underlined: limit 9 to english language and last 7 years] | [underlined: 105]
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to October 13, 2021 | 1 | (Outpatients AND (Allergy OR Immunology OR Cardiology OR Critical Care OR Respiratory Therapy OR Dermatology OR Diabetes Mellitus OR Gastroenterology OR HIV OR Hepatitis B OR Hepatitis C OR Infectious Disease Medicine OR Nephrology OR Neurology OR Medical Oncology OR Optometry OR Pain Management OR Rheumatology OR Sleep Medicine Specialty)).kw. | 0
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to October 13, 2021 | 2 | (((Outpatient$1 OR (outpatient adj3 (care OR clinic$1))) AND (vascular medicine OR cardiology OR angiology OR cardiovascular disease OR dermatology OR critical care OR ICU OR intensive care OR endocrinology OR gastroenterology OR sleep medicine OR hepatology OR infectious disease$1 OR nephrology OR neurology OR nervous system OR oncology OR cancer OR optometry OR rheumatology OR immunology OR allergy OR HIV OR AIDS OR hepatitis OR diabetes OR pulmonary OR respiratory therap*))).ti,ab. | 62
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to October 13, 2021 | 3 | 1 OR 2 | 62
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to October 13, 2021 | 4 | (Personnel Staffing OR Scheduling OR Shift Work Schedule OR Work Schedule Tolerance OR Workload OR Workforce OR Nursing Models OR Resource Allocation).kw. | 15
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to October 13, 2021 | 5 | (schedule* OR staff* OR personnel OR workload$1 OR work hours OR work load$1 OR nursing model$1 OR staffing model$1 OR (resource adj1 allocation) OR resource$1).ti,ab. | 820
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to October 13, 2021 | 6 | 4 OR 5 | 826
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to October 13, 2021 | 7 | 3 AND 6 | 8
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to October 13, 2021 | 8 | Limit 7 to last 7 years | 3

Search for current systematic reviews (limited to last 7 years); Date Searched: 10-21-21
B. Non-bibliographic databases | Evidence | Results
AHRQ: evidence reports, technology assessments, US Preventative Services Task Force Evidence Synthesis | http://www.ahrq.gov/research/findings/evidence-based-reports/search.html; Search: staffing models | 0
CADTH | https://www.cadth.ca; Search: staffing models | 0
ECRI Institute | https://guidelines.ecri.org/; Search: staffing models | 0
HTA: Health Technology Assessments (UP TO 2016) | http://www.ohsu.edu/xd/education/library/; Search: See Cochrane search above | 0
NHS Evidence | http://www.evidence.nhs.uk/default.aspx; Search: staffing models; outpatient | 0
EPPI-Centre | http://eppi.ioe.ac.uk/cms/Default.aspx?tabid=62; Use browser search function [CNTL + F] for keyword search; Search: staffing models; outpatient | 0
NLM | http://www.ncbi.nlm.nih.gov/books; Search: staffing models; outpatient | 0
VA Products - VATAP, PBM and HSR&D publications | A. http://www.hsrd.research.va.gov/research/default.cfm; B. http://www.research.va.gov/research_topics/; C. https://va.dimensions.ai/discover/publication; Search: staffing models; outpatient; How nursing staff skill mix, education and experience modify patient acuity-based estimates of required unit staffing.; https://www.hsrd.research.va.gov/research/abstracts.cfm?Project_ID=2141706986 | 1

#### PRIMARY STUDIES

Search for primary literature; Date searched: 10-21-21
MEDLINE [Ovid MEDLINE(R) ALL 1946 to October 18, 2021]
# | Search Statement | Results
[underlined: 1] | (Outpatients/ AND (“Allergy and Immunology”/ OR Cardiology/ OR Critical Care/ OR Respiratory Therapy/ OR Dermatology/ OR exp Diabetes Mellitus/ OR Gastroenterology/ OR HIV/ OR Hepatitis B/ OR Hepatitis C/ OR Infectious Disease Medicine/ OR Nephrology/ OR Neurology/ OR exp Medical Oncology/ OR Optometry/ OR Pain Management/ OR Rheumatology/ OR Sleep Medicine Specialty/)) OR (((Outpatient$1 OR (outpatient adj3 (care OR clinic$1))) AND (vascular medicine OR cardiology OR angiology OR cardiovascular disease OR dermatology OR critical care OR ICU OR intensive care OR endocrinology OR gastroenterology OR sleep medicine OR hepatology OR infectious disease$1 OR nephrology OR neurology OR nervous system OR oncology OR cancer OR optometry OR rheumatology OR immunology OR allergy OR HIV OR AIDS OR hepatitis OR diabetes OR pulmonary OR respiratory therap*))).ti,ab. | 55771
[underlined: 2] | Personnel Staffing and Scheduling/ OR Shift Work Schedule/ OR Work Schedule Tolerance/ OR Workload/ OR Workforce/ OR Models, Nursing/ OR Resource Allocation/ OR (schedule* OR staff* OR personnel OR workload$1 OR work hours OR work load$1 OR nursing model$1 OR staffing model$1 OR (resource adj1 allocation) OR resource$1).ti,ab. | 872034
[underlined: 3] | 1 AND 2 | 5516
4 | Limit 3 to english language | 5074
CINAHL
# | Search Statement | Results
1 | (MH “Outpatients”) AND ((MH “Allergy and Immunology”) OR (MH “Cardiology”) OR (MH “Critical Care”) OR (MH “Respiratory Therapy”) OR (MH “Dermatology”) OR (MH “Diabetes Mellitus+”) OR (MH “Gastroenterology Care”) OR (MH “Human Immunodeficiency Virus”) OR (MH “Hepatitis B”) OR (MH “Hepatitis C”) OR (MH “Communicable Diseases”) OR (MH “Nephrology”) OR (MH “Neurology”) OR (MH “Oncology+”) OR (MH “Optometry”) OR (MH “Pain Management”) OR (MH “Rheumatology”) OR (MH “Sleep Disorders”)) | 3022
2 | TI ( (((Outpatient$1 OR (outpatient N3 (care OR clinic$1))) AND (vascular medicine OR cardiology OR angiology OR cardiovascular disease OR dermatology OR critical care OR ICU OR intensive care OR endocrinology OR gastroenterology OR sleep medicine OR hepatology OR infectious disease$1 OR nephrology OR neurology OR nervous system OR oncology OR cancer OR optometry OR rheumatology OR immunology OR allergy OR HIV OR AIDS OR hepatitis OR diabetes OR pulmonary OR respiratory therap*))) ) OR AB ( (((Outpatient$1 OR (outpatient N3 (care OR clinic$1))) AND (vascular medicine OR cardiology OR angiology OR cardiovascular disease OR dermatology OR critical care OR ICU OR intensive care OR endocrinology OR gastroenterology OR sleep medicine OR hepatology OR infectious disease$1 OR nephrology OR neurology OR nervous system OR oncology OR cancer OR optometry OR rheumatology OR immunology OR allergy OR HIV OR AIDS OR hepatitis OR diabetes OR pulmonary OR respiratory therap*))) ) | 2073
3 | 1 OR 2 | 4990
4 | (MH “Personnel Staffing and Scheduling”) OR (MH “Shiftwork”) OR (MH “Workload”) OR (MH “Workforce”) | 52060
5 | TI ( (schedule* OR staff* OR personnel OR workload$1 OR work hours OR work load$1 OR nursing model$1 OR staffing model$1 OR (resource N1 allocation) OR resource$1) ) OR AB ( (schedule* OR staff* OR personnel OR workload$1 OR work hours OR work load$1 OR nursing model$1 OR staffing model$1 OR (resource N1 allocation) OR resource$1) ) | 203450
6 | 4 OR 5 | 241628
7 | 3 AND 6 | 307
8 | Limit 7 to English language | 292

### APPENDIX B EXCLUDED STUDIES

Exclude reasons: 1=Ineligible population, 2=Ineligible intervention, 3=Ineligible comparator, 4=Ineligible outcome, 5=Ineligible timing, 6=Ineligible study design, 7=Ineligible publication type 8=Outdated or ineligible systematic review, 9=Non-English language, 10=Unable to obtain full text

Citation | Exclude Reason
Agrawal D, Jain R. Staffing at Ambulatory Endoscopy Centers in the United States: Practice, Trends, and Rationale. Gastroenterology Research & Practice. 2018;2018:9463670 30302089 30302089 | E4
Albarrati Am Pt P. Outpatient physical therapy cardiovascular assessment: Physical therapist perspective and experience. Physiotherapy Theory & Practice. 2019;35(9):843–850 29596007 | E1
Allen JI, Aldrich L, Moote M. Building a Team-Based Gastroenterology Practice With Advanced Practice Providers. Gastroenterology & Hepatology. 2019;15(4):213–220 31435200 | E4
Allison TG, Squires RW, Johnson BD & Gau GT. Achieving National Cholesterol Education Program goals for low-density lipoprotein cholesterol in cardiac patients: importance of diet, exercise, weight control, and drug therapy. Mayo Clinic Proceedings. 1999; 74(5): 466–473.10319076 | E4
Al-Shamsi HO, Alhazzani W, Alhuraiji A, . A Practical Approach to the Management of Cancer Patients During the Novel Coronavirus Disease 2019 (COVID-19) Pandemic: An International Collaborative Group. Oncologist. 2020;25(6):e936–e945 32243668 | E4
Anil G, Hirisave Krishna B, Johnson CC, Richards SL, Bhandari P. Outpatient Practice Reactivation in an Integrated Community Practice During the COVID-19 Pandemic. Telemedicine Journal & E Health. 2021. p. 22. | E2
Ansari M, Alexander M, Tutar A, Bello D, Massie BM. Cardiology participation improves outcomes in patients with new-onset heart failure in the outpatient setting. Journal of the American College of Cardiology. 2003;41(1):62–8 12570946 | E1
Atanda A, Shapiro NL, Stubbings J, Groo V. Implementation of a New Clinic-Based, Pharmacist-Managed PCSK9 Inhibitor Consultation Service. Journal of Managed Care & Specialty Pharmacy. 2017;23(9):918–925 28854074 | E4
Atlas KR, Forbes M, Riches J, . The scope of hospital medicine practice at night: a national survey of night shift hospitalists. Hospital Practice. 2021;49(4):292–297 34030568 | E1
Awad C, Canneva A, Chiasson CO, . PHIRST Trial - pharmacist consults: prioritization of HIV-patients with a referral screening tool. AIDS Care. 2017;29(11):1463–1472 28614952 | E1
Bellanti JA. The role of the allergist/immunologist in the COVID-19 pandemic: A Janus-faced presentation. Allergy & Asthma Proceedings. 2020;41(6):397–412 32797762 | E1
Benedetti R, Flock B, Pedersen S, Ahern M. Improved clinical outcomes for fee-for-service physician practices participating in a diabetes care collaborative. Joint Commission Journal on Quality & Safety. 2004;30(4):187–194 15085784 | E1
Benjamin EM, Schneider MS, Hinchey KT. Implementing practice guidelines for diabetes care using problem-based learning: a prospective controlled trial using firm systems. Diabetes Care. 1999;22(10):1672–1678. doi:10.2337/diacare.22.10.1672 10526733 | E1
Berk RA, Baigis-Smith J, Nanda JP. Health care needs of persons with HIV/AIDS in various settings. Western Journal of Nursing Research. 1995;17(6):647–71 8597231 | E2
Berkhof FF, Hesselink AM, Vaessen DL, Uil SM, Kerstjens HA, van den Berg JW. The effect of an outpatient care on-demand-system on health status and costs in patients with COPD. A randomized trial. Respiratory Medicine. 2014;108(8):1163–70 24931900 | E5
Berkhof FF, van den Berg JW, Uil SM, Kerstjens HA. Telemedicine, the effect of nurse-initiated telephone follow up, on health status and health-care utilization in COPD patients: a randomized trial. Respirology. 2015;20(2):279–85 25400242 | E2
Bess KD, Adams J, Watt MH, . Providers’ Attitudes Towards Treating Depression and Self-Reported Depression Treatment Practices in HIV Outpatient Care. AIDS Patient Care & STDs. 2013;27(3):171–180. doi:10.1089/apc.2012.0406 23442030 | E2
Bickell NA, Young GJ. Coordination of care for early-stage breast cancer patients. Journal of General Internal Medicine. 2001;16(11):737–42 11722686 | E4
Bjegovich-Weidman M, Kahabka J, Bock A, Frick J, Kowalski H, Mirro J. Development by a Large Integrated Health Care System of an Objective Methodology for Evaluation of Medical Oncology Service Sites. Journal of Oncology Practice/American Society of Clinical Oncology. 2012;8(2):70 | E4
Blay N, Cairns J, Chisholm J, O’Baugh J. Research into the workload and roles of oncology nurses within an outpatient oncology unit. European Journal of Oncology Nursing. 2002;6(1):6–12; discussion 13–4 12849602 | E5
Bozzo J, Carlson B, Diers D. Using hospital data systems to find target populations: new tools for clinical nurse specialists. Clinical Nurse Specialist. 1998;12(2):86–91 9708115 | E2
Bukhari M, Dixey J, Deighton C. A survey of new to follow-up ratios in rheumatology outpatient departments. Clinical Medicine. 2011;11(1):99–100 21404801 | E5
Bunnell CA, Gross AH, Weingart SN, . High performance teamwork training and systems redesign in outpatient oncology. BMJ Quality & Safety. 2013;22(5):405–13 | E2
Byock I, Twohig JS, Merriman M, Collins K. Promoting excellence in end-of-life care: a report on innovative models of palliative care. Journal of Palliative Medicine. 2006;9(1):137–51 16430353 | E1
Carroll JJ, Colasanti J, Lira MC, Del Rio C, Samet JH. HIV Physicians and Chronic Opioid Therapy: It’s Time to Raise the Bar. AIDS & Behavior. 2019;23(4):1057–1061 30519904 | E6
Chang BP, Rostanski S, Willey J, . Safety and Feasibility of a Rapid Outpatient Management Strategy for Transient Ischemic Attack and Minor Stroke: The Rapid Access Vascular Evaluation-Neurology (RAVEN) Approach. Annals of Emergency Medicine. 2019;74(4):562–571 31326206 | E2
Chin MH, Zhang JX, Merrell K. Specialty differences in the care of older patients with diabetes. Medical Care. 2000;38(2):131–40 10659687 | E2
Chung MH, Hung KC, Chiou JF, Fang HF, Chiu CH. Nursing manpower forecast for cancer patients. Computer Methods & Programs in Biomedicine. 2021;201:105967 33588340 | E5
Clapp JD, Burke AC. Supervisor ideology and organizational response: HIV/AIDS prevention in outpatient substance abuse treatment units. Administration in Social Work. 1997;21(1):49–64 10166759 | E7
Cochrane B, Foster J, Boyd R, Atlantis E. Implementation challenges in delivering team-based care (‘TEAMcare’) for patients with chronic obstructive pulmonary disease in a public hospital setting: a mixed methods approach. BMC Health Services Research. 2016;16(a):347+A37 27488412 | E2
Colubi MM, Perez-Elias MJ, Elias L, . Missing scheduled visits in the outpatient clinic as a marker of short-term admissions and death. HIV Clinical Trials. 2012;13(5):289–95 23134630 | E2
Colvin L, Cartwright A, Collop N, . Advanced practice registered nurses and physician assistants in sleep centers and clinics: a survey of current roles and educational background. Journal of Clinical Sleep Medicine. 2014;10(5):581–7 24812545 | E4
Coombes CE, Gregory ME. The Current and Future Use of Telemedicine in Infectious Diseases Practice. Current Infectious Disease Reports. 2019;21(11):41 31630276 | E6
Covington CC, Muckler VC, Sheldon L, Alexander R, Morgan B. Improving Emergency Airway Knowledge and Self-Efficacy Levels of Outpatient Gastroenterology Staff via Implementation of Online Education and In Situ Simulation. Gastroenterology Nursing. 2019;42(3):242–250 31145248 | E2
Craig K, Flaherty-Quemere A. Implementing an automated acuity tool for scoring case management cases and caseloads at Blue Cross Blue Shield of Massachusetts. Professional Case Management. 2009;14(4):185–91 19625937 | E4
Crowther M. Optimal management of outpatients with heart failure using advanced practice nurses in a hospital-based heart failure center. Journal of the American Academy of Nurse Practitioners. 2003;15(6):260–5 12861892 | E5
Dandachi D, Dang BN, Lucari B, Teti M, Giordano TP. Exploring the Attitude of Patients with HIV About Using Telehealth for HIV Care. AIDS Patient Care & STDs. 2020;34(4):166–172 32324481 | E2
Dave SS, Miles K, Griffiths C, Mercey DE, Edwards SG. Is it time to rethink the roles of health professionals in the HIV outpatient setting? Sexually Transmitted Infections. 2004;80(2):153–4 15054186 | E7
Davis MP, Strasser F, Cherny N. How well is palliative care integrated into cancer care? A MASCC, ESMO, and EAPC Project. Supportive Care in Cancer. 2015;23(9):2677–85 25676486 | E1
Davis TME, Drinkwater JJ, Fegan PG, Chikkaveerappa K, Sillars B, Davis WA. Community-based management of complex type 2 diabetes: adaptation of an integrated model of care in a general practice setting. Internal Medicine Journal. 2021;51(1):62–68 31661182 | E5
De la Cruz MG, Wong A, Castro D, Bruera E. Snapshot of an outpatient supportive care center at a comprehensive cancer center. Journal of Clinical Oncology. 2016;34(29):145–145. doi:10.1200/jco.2016.34.26_suppl.145 | E2
Dechert TA, Sarani B, McMaster M, . Medical emergency team response for the non-hospitalized patient. Resuscitation. 2013;84(3):276–9 22776516 | E2
Donohue RB. Use of evidence-based practice by outpatient oncology nurses in the management of cancer-related pain and fatigue. University of Utah; 2012. | E7
Dumkow LE, Beuschel TS, Brandt KL. Expanding Antimicrobial Stewardship to Urgent Care Centers Through a Pharmacist-Led Culture Follow-up Program. Infectious Diseases & Therapy. 2017;6(3):453–459 28853035 | E1
Eisenberg S. Ambulatory oncology clinics. Oncology nurses juggle staffing and scheduling in the outpatient setting. ONS Connect. 2009;24(8):6–8 | E4
Emamifar A, van Bui Hansen MH, Jensen Hansen IM. The ratio of nurse consultation and physician efficiency index of senior rheumatologists is significantly higher than junior physicians in rheumatology residency training: A new efficiency measure in a cohort, exploratory study. Medicine. 2017;96(14):e6601 28383442 | E4
Enterline JP, Majidi FM, Ogorzalek LL, . Integrated ambulatory care services in oncology. Proceedings - the Annual Symposium on Computer Applications in Medical Care. 1992:197–201 | E4
Erdmann CM. The value of the intersystem model for cosmetic nursing practice. Dermatology Nursing. 2003;15(4):335–8 14515613 | E4
Essien UR, He W, Ray A, . Disparities in Quality of Primary Care by Resident and Staff Physicians: Is There a Conflict Between Training and Equity? Journal of General Internal Medicine. 2019;34(7):1184–1191 30963439 | E1
Fan VS, Gaziano JM, Lew R, . A comprehensive care management program to prevent chronic obstructive pulmonary disease hospitalizations: a randomized, controlled trial. Annals of Internal Medicine. 2012;156(10):673–83 22586006 | E2
Ferre-Ybarz L, Salinas Argente R, Nevot Falco S, . Allergy medical care network: a new model of care for specialties. Allergologia et Immunopathologia. 2015;43(1):48–56 24485937 | E5
Finlay E, Newport K, Sivendran S, Kilpatrick L, Owens M, Buss MK. Models of Outpatient Palliative Care Clinics for Patients With Cancer. Journal of Oncology practice/American Society of Clinical Oncology. 2019;15(4):187–193 | E1
Flemming KD, Allison TG, Covalt JL, Herzig DE, Brown RD. Utility of a post-hospitalization stroke prevention program managed by nurses. Hospital Practice. 2013;41(3):70–9 23948623 | E1
Foisy MM, Tseng A, Blaikie N. Pharmacists’ provision of continuity of care to patients with human immunodeficiency virus infection. American Journal of Health-System Pharmacy. 1996;53(9):1013–7 8744462 | E4
Freeman WD, Gronseth G, Eidelman BH. Invited article: is it time for neurohospitalists? Neurology. 2008;70(15):1282–1288. doi:10.1212/01.wnl.0000308949.45423.13 18337585 | E4
Frey MK, Fowlkes RK, Badiner NM, . Gynecologic oncology care during the COVID-19 pandemic at three affiliated New York City hospitals. Gynecologic Oncology. 2020;159(2):470–475 32981694 | E2
Frogge MH. Streamlining outpatient cisplatin therapy to meet the challenges of today. A65. 1989;5(2 Suppl 1):21–8 | E4
Garvey C, Carlin B, Raskin J. Program organization in pulmonary rehabilitation. Clinics in Chest Medicine. 2014;35(2):423–8 24874136 | E4
Giannitrapani KF, Silveira MJ, Azarfar A, . Cross Disciplinary Role Agreement is Needed When Coordinating Long-Term Opioid Prescribing for Cancer: a Qualitative Study. Journal of General Internal Medicine. 2021;36(7):1867–1874 33948790 | E4
Glare PA, Semple D, Stabler SM, Saltz LB. Palliative care in the outpatient oncology setting: evaluation of a practical set of referral criteria. Journal of oncology practice/American Society of Clinical Oncology. 2011;7(6):366–70 | E1
Graney BA, Au DH, Baron AE, . Advancing Symptom Alleviation with Palliative Treatment (ADAPT) trial to improve quality of life: a study protocol for a randomized clinical trial. Trials. 2019;20(1):355 31196156 | E4
Granger CL, Parry SM, Denehy L, Remedios L. Evidence, education and multi-disciplinary integration are needed to embed exercise into lung cancer clinical care: A qualitative study involving physiotherapists. Physiotherapy Theory & Practice. 2018. p. 852–860.29336644 | E10
Greenhalgh T, Shaw S, Wherton J, . Real-World Implementation of Video Outpatient Consultations at Macro, Meso, and Micro Levels: Mixed-Method Study. Journal of Medical Internet Research. 2018;20(4):e150 29625956 | E2
Hall-Smith J, Ball C, Coakley J. Follow-up services and the development of a clinical nurse specialist in intensive care. Intensive & Critical Care Nursing. 1997;13(5):243–248 9538710 | E1
Hamel LM, Chapman R, Eggly S, . Measuring the use of examination room time in oncology clinics: a novel approach to assessing clinic efficiency and patient flow. Journal of Oncology Practice/American Society of Clinical Oncology. 2014;10(6):e385–9 | E2
Harris MG, Bean CA. Changing the role of the nurse in the hematology-oncology outpatient setting. Oncology Nursing Forum. 1991;18(1):43–6 2003115 | E4
Hashemi-Sadraei N, Sasankan S, Crozier N, . Improving Outpatient Infusion Clinic Wait Times at a Comprehensive Cancer Center. JCO Oncology Practice. 2021: OP2100118 | E2
Hemingway JF, Singh N, Starnes BW. Emerging practice patterns in vascular surgery during the COVID-19 pandemic. Journal of Vascular Surgery. 2020;72(2):396–402 32361072 | E1
Hendershot E, Murphy C, Doyle S, Van-Clieaf J, Lowry J, Honeyford L. Outpatient chemotherapy administration: decreasing wait times for patients and families. Journal of Pediatric Oncology Nursing. 2005;22(1):31–37 15574724 | E1
Henninger D, Dailey C. Measuring nursing workload in an outpatient department. Journal of Nursing Administration. 1983;13(9):20–3 | E2
Ho ET. Improving waiting time and operational clinic flow in a tertiary diabetes center. BMJ Quality Improvement Reports. 2014;2(2) | E5
Hoberty PD, Chiu CY, Hoberty RJ. Staffing exercise sessions in pulmonary rehabilitation. Respiratory Care. 2001;46(7):694–7 11403700 | E7
Hodgins FE, Lang JM, Malseptic GG, Melby LH, Connolly KA. Coordinating Outpatient Care for Pregnant and Postpartum Women with Opioid Use Disorder: Implications from the COACHH Program. Maternal & Child Health Journal. 2019;23(5):585–591 30604105 | E4
Hollinworth H. Nurses’ assessment and management of pain at wound dressing changes. Journal of Wound Care. 1995;4(2):77–83 7600340 | E2
Hook A. Breast cancer navigation and patient satisfaction: exploring a community-based patient navigation model in a rural setting. Oncology Nursing Forum.2012;39(4). | E4
Hoskins P, Alford J, Fowler P, . Outpatient stabilization programme--an innovative approach in the management of diabetes. Diabetes Research. 1985;2(2):85–8 3899465 | E5
Hui D, Hannon BL, Zimmermann C, Bruera E. Improving patient and caregiver outcomes in oncology: Team-based, timely, and targeted palliative care. CA: a Cancer Journal for Clinicians. 2018;68(5):356–376 30277572 | E1
Israni A, Dean CE, Salkowski N, . Variation in structure and delivery of care between kidney transplant centers in the United States. Transplantation. 2014;98(5):520–8 24825518 | E2
James ND, Guerrero D, Brada M. Who should follow up cancer patients? Nurse specialist based outpatient care and the introduction of a phone clinic system. Clinical Oncology. 1994. p. 283–7.7826919 | E5
Jeger RV, Jorg L, Rickenbacher P, Pfisterer ME, Hoffmann A. Benefit of outpatient cardiac rehabilitation in under-represented patient subgroups. Journal of Rehabilitation Medicine. 2007;39(3):246–51 17468794 | E2
Jerant A, Kravitz RL, Tancredi D, . Training Primary Care Physicians to Employ Self-Efficacy-Enhancing Interviewing Techniques: Randomized Controlled Trial of a Standardized Patient Intervention. Journal of General Internal Medicine. 2016;31(7):716–22 26956140 | E1
Jessup M, Albert NM, Lanfear DE, . ACCF/AHA/HFSA 2011 survey results: current staffing profile of heart failure programs, including programs that perform heart transplant and mechanical circulatory support device implantation. Journal of Cardiac Failure. 2011;17(5):349–58 21549290 | E2
Jones C, Macmillan RR, Griffiths RD. Providing psychological support for patients after critical illness. Clinical Intensive Care.1994. p. 176–9.10150543 | E2
Jorgensen L, Jacobsen HR, Pedersen B, Uhrenfeldt L. Calling an Oncological Emergency Telephone to Seek Advice: An Interview Study. Cancer Nursing. 2021;44(2):98–105 31895172 | E7
Karus D, Raveis VH, Marconi K, . Service needs of patients with advanced HIV disease: a comparison of client and staff reports at three palliative care projects. AIDS Patient Care & STDs. 2004;18(3):145–158. doi:10.1089/108729104322994838 15104875 | E1
Kasle DA, Torabi SJ, Savoca EL, Judson BL, Manes RP. Outpatient Otolaryngology in the Era of COVID-19: A Data-Driven Analysis of Practice Patterns. Otolaryngology - Head & Neck Surgery. 2020;163(1):138–144 32393101 | E2
Katz MH, Slack R, Bruno M, . Outpatient virtual clinical encounters after complex surgery for cancer: a prospective pilot study of “TeleDischarge”. Journal of Surgical Research. 2016;202(1):196–203 | E1
Kegel LM. Advanced practice nurses can refine the management of heart failure. Clinical Nurse Specialist. 1995;9(2):76–81 7600486 | E4
Kenealy TW, Parsons MJ, Rouse AP, . Telecare for diabetes, CHF or COPD: effect on quality of life, hospital use and costs. A randomised controlled trial and qualitative evaluation. PLoS ONE. 2015;10(3):e0116188 25768023 | E2
Kennedy LC, Wong KM, Kamat NV, . Untangling the Multidisciplinary Care Web: Streamlining Care Through an Immune-Related Adverse Events (IRAE) Tumor Board. Targeted Oncology. 2020;15(4):541–548 32710246 | E5
Kenney-Lueptow J. Inpatient Navigation: Utilizing Nurse Navigation Principles to Transition Patients Through Hospitalization, Discharge, and Outpatient Care. Journal of Oncology Navigation & Survivorship. 2020;11(1):7–13 | E1
Klafke N, Mahler C, von Hagens C, Blaser G, Bentner M, Joos S. Developing and implementing a complex Complementary and Alternative (CAM) nursing intervention for breast and gynecologic cancer patients undergoing chemotherapy--report from the CONGO (complementary nursing in gynecologic oncology) study. Supportive Care in Cancer. 2016;24(5):2341–2350 26630949 | E2
Klingenheben T, Albakri A, T MH. Transtelephonic ECG Monitoring to Guide Outpatient Antiarrhythmic Drug Therapy in Patients With Non-Permanent Atrial Fibrillation: Efficacy and Safety From a Single-Center Experience. Journal of Atrial Fibrillation. 2019;11(6):2161 31384368 | E2
Knight V, Guy RJ, Handan W, Lu H, McNulty A. It is more efficient to type: innovative self-registration and appointment self-arrival system improves the patient reception process. Sexually Transmitted Diseases. 2014;41(6):392–4 24825337 | E2
Knox A. Ambulatory care unit role optimization for the specialized oncology nurse. Canadian Oncology Nursing Journal. 2020;30(3):159–168 33118976 | E7
Konstan MW, Butler SM, Schidlow DV, Morgan WJ, Julius JR, Johnson CA. Patterns of medical practice in cystic fibrosis: part I. Evaluation and monitoring of health status of patients. Investigators and Coordinators of the Epidemiologic Study of Cystic Fibrosis. Pediatric Pulmonology. 1999;28(4):242–7 10497372 | E2
Krantz, M. J., Havranek, E. P., Haynes, D. K., Smith, I., Bucher-Bartelson, B., & Long, C. S. (2008). Inpatient initiation of β-blockade plus nurse management in vulnerable heart failure patients: a randomized study. Journal of Cardiac Failure, 14(4), 303–309.18474343 | E1
Kuhns WJ, Allen FH, Jr., Kellner A. Blood banking as a professional discipline in medicine. Transfusion. 1975;15(2):152–8 1118882 | E2
Kurian T, Stranges E, Czerlanis C. Standardization of the Discharge Process for Inpatient Hematology and Oncology Using Plan-Do-Study-Act Methodology Improves Follow-Up and Patient Hand-Off. Federal Practitioner. 2021;38(Suppl 2):S50–S56 34177241 | E2
Lamkin L, Rosiak J, Buerhaus P, Mallory G, Williams M. Oncology Nursing Society Workforce Survey. Part II: perceptions of the nursing workforce environment and adequacy of nurse staffing in outpatient and inpatient oncology settings. Oncology Nursing Forum. 2002;29(1):93–100 11817495 | E2
Larenas-Linnemann DE, Gupta P, Mithani S, Ponda P. Survey on immunotherapy practice patterns: dose, dose adjustments, and duration. Annals of Allergy, Asthma, & Immunology. 2012;108(5):373–378.e3 | E2
LeBlanc ES, Rosales AG, Kachroo S, Mukherjee J, Funk KL, Nichols GA. Do Patient or Provider Characteristics Impact Management of Diabetes? American Journal of Managed Care. 2015;21(9):597–606 | E2
Lee PW, Markle PS, West AN, Lee RE. Use and Quality of Care at a VA Outreach Clinic in Northern Maine. Journal of Primary Care & Community Health. 2012;3(3):159–63 | E1
Lewandowski L. Developing collaborative partnerships between inpatient nephrology and outpatient dialysis units. Advances in Renal Replacement Therapy. 1995;2(4):371–2 8591128 | E6
Lewis R, Hendry M. A review comparing the effectiveness of nurse-led follow up for cancer with conventional care. Nursing Times. 2009;105(37):25–7 | E5
Lopez-Martinez N, Segu JL, Vazquez-Castro J, . Analysis of the implementation of a personalized care model in diabetes mellitus as an example of chronic disease with information and communication technology support. Expert Review of Pharmacoeconomics & Outcomes Research. 2017;17(2):141–148 28403728 | E5
Lucciola ME, Nelson NM, Rea JM, Boudreaux AJ, Fedderson DJ, Hodge NS. Clinical Nurse Specialist Impact on COVID-19 Preparation at a Military Treatment Facility. Clinical Nurse Specialist. 2021;35(3):138–146 33793176 | E1
Lynn SE. The development of a time-based nursing information system in dermatology outpatients and day therapy areas. Journal of Nursing Management. 2002;10(3):153–160. doi:10.1046/j.1365-2834.2002.00322.x 11982782 | E4
Maarseveen TD, Maurits MP, Niemantsverdriet E, van der Helm-van Mil AHM, Huizinga TWJ, Knevel R. Handwork vs machine: a comparison of rheumatoid arthritis patient populations as identified from EHR free-text by diagnosis extraction through machine-learning or traditional criteria-based chart review. Arthritis Research & Therapy. 2021;23(1):174 34158089 | E5
MacKinnon NJ, Flagstad MS, Peterson CR, Mesch-Beatty K. Disease management program for asthma: baseline assessment of resource use. American Journal of Health-System Pharmacy. 1996;53(5):535–41 8697013 | E2
Mahaffey K, Stanisstreet D, Ford M, . Role of the diabetes inpatient specialist nurse in preventing hospital admission from A&E. Journal of Diabetes Nursing. 2012;16(2):57–61 | E1
Maltoni M, Scarpi E, Dall’Agata M, . Systematic versus on-demand early palliative care: A randomised clinical trial assessing quality of care and treatment aggressiveness near the end of life. European Journal of Cancer. 2016;69:110–118 27821313 | E1
Mannel R, Mannel RS. Staffing for hospital lactation programs: recommendations from a tertiary care teaching hospital. Journal of Human Lactation. 2006;22(4):409–17 17062786 | E1
Martin S. Developing the nurse practitioner’s role in minor surgery. Nursing Times. 2002;98(33):39–40 | E1
Matsuda A, Kobayashi M, Sakakibara Y, . Quality of life of lung cancer patients receiving outpatient chemotherapy. Experimental & Therapeutic Medicine. 2011;2(2):291–294 22977500 | E5
Matta ME, Patterson SS. Evaluating multiple performance measures across several dimensions at a multi-facility outpatient center. Health Care Management Science. 2007;10(2):173–94 17608058 | E2
Matthews J. Earlier access to palliative medicine: An experience of integration into a community oncology practice. Journal of Clinical Oncology. 2016;34(29):92–92. doi:10.1200/jco.2016.34.26_suppl.92 | E7
Maxwell S, Wellman LG, Savage T. Merging Two Robust Women’s Services in Alignment With a Comprehensive Nursing Strategic Business Plan. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2014;43(Supp 1):S49–S50. doi:10.1111/1552-6909.12434 | E7
McBride A, Campen CJ, Camamo J, . Implementation of a pharmacy-managed program for the transition of chemotherapy to the outpatient setting. American Journal of Health-System Pharmacy. 2018;75(9):e246–e258 29691269 | E2
McCarley PB, Hudson M, Kammerer J. Staffing: PCT certification and education: the cart before the horse? Nephrology News & Issues. 2009;23(11):4p–4p | E7
McNett M, Goldenberg D, Schaefer C, . Treatment patterns among physician specialties in the management of fibromyalgia: results of a cross-sectional study in the United States. Current Medical Research & Opinion. 2011;27(3):673–83 21294700 | E2
Mettlin C, Kizilbash M, Michalek A. Hospital-based cancer detection programs for the community. Journal of Surgical Oncology. 1980;15(3):249–57 7431922 | E2
Milne E, Hutchinson A, Platt P, Parkin D. An evaluation of ambulatory visit groups in rheumatology out-patients. Journal of Public Health Medicine. 1994;16(1):41–9 8037952 | E1
Mims RB, Thomas LL, Conroy MV. Physician house calls: a complement to hospital-based medical care. Journal of the American Geriatrics Society. 1977;25(1):28–34 830712 | E1
Min L, Cigolle CT, Bernstein SJ, . Diabetes care improvement in pharmacist-versus nurse-supported patient-centered medical homes. American Journal of Managed Care. 2017;23(11):e374–e381 | E5
Mitchell C, Catalan J, McIntosh C, Feher MD. Joint liaison psychiatry-diabetes clinic: a new specialist service. Diabetic Medicine. 2000;17(6):481–3 10975219 | E2
Mock V, Burke MB, Sheehan P, . A nursing rehabilitation program for women with breast cancer receiving adjuvant chemotherapy. Oncology Nursing Forum. 1994;21(5):899–907; discussion 908 7937251 | E2
Morrow GR, Craytor JK, Brown J, Fass M. Nurses’ perceptions of themselves, cancer nurses, typical, ideal and cancer patients. Perceptual & Motor Skills. 1976;43(3 Pt 2):1083–91 1012886 | E2
Moscovice IS, Casey MM, Wu Z. Disparities in Geographic Access to Hospital Outpatient Pulmonary Rehabilitation Programs in the United States. Chest. 2019;156(2):308–315 30978331 | E7
Mullally DI, Sogn DD, Goldstein RA, Cohen SG. Academic manpower needs in allergy and clinical immunology. Journal of Allergy & Clinical Immunology. 1983;72(3):252–4 | E7
Musellim B, Borekci S, Uzan G, . What should be the appropriate minimal duration for patient examination and evaluation in pulmonary outpatient clinics? Annals of Thoracic Medicine. 2017;12(3):177–182 28808489 | E5
Mutsekwa RN, Canavan R, Whitfield A, Spencer A, Angus RL. Dietitian first gastroenterology clinic: an initiative to reduce wait lists and wait times for gastroenterology outpatients in a tertiary hospital service. Frontline Gastroenterology. 2019;10(3):229–235 31281623 | E5
Myers Virtue S, Howrey HL, Duffy NM, Wallace M. Shifting psychosocial oncology care to telepsychology during the COVID-19 pandemic. Journal of Psychosocial Oncology. 2021. p. 416–427.33792503 | E1
Nelson CA, Takeshita J, Wanat KA, . Impact of store-and-forward (SAF) teledermatology on outpatient dermatologic care: A prospective study in an underserved urban primary care setting. Journal of the American Academy of Dermatology. 2016;74(3):484–90.e1 26679528 | E1
Nicholson C, Bowler S, Jackson C, Schollay D, Tweeddale M, O’Rourke P. Cost comparison of hospital- and home-based treatment models for acute chronic obstructive pulmonary disease. Australian Health Review. 2001;24(4):181–7 11842709 | E5
Nolan K, Schall MW, Erb F, Nolan T. Using a framework for spread: The case of patient access in the Veterans Health Administration. Joint Commission Journal on Quality & Patient Safety. 2005;31(6):339–47 15999964 | E2
Norman PS, Biermann CW, Frick OL, . Physician manpower in allergy and immunology. Journal of Allergy & Clinical Immunology. 1978;62(1):61–6 | E2
O’Brien CW, Breland JY, Slightam C, Nevedal A, Zulman DM. Engaging high-risk patients in intensive care coordination programs: the engagement through CARInG framework. Translational Behavioral Medicine. 2018;8(3):351–356 29800395 | E2
Ocker BM, Plank DM. The research nurse role in a clinic-based oncology research setting. Cancer Nursing. 2000;23(4):286–92; quiz 293–4 10939176 | E2
Okera M, Baker NA, Hayward AM, Selva-Nayagam S. Oncology workforce issues: the challenge of the outpatient clinic. Internal Medicine Journal. 2011;41(6):499–503 21707896 | E2
Okuboyejo S, Eyesan O. mHealth: Using Mobile Technology to Support Healthcare. Online Journal of Public Health Informatics. 2014;5(3):233 24678384 | E2
Patel SD, Nguyen PAA, Bachler M, Atkinson B. Implementation of postdischarge follow-up telephone calls at a comprehensive cancer center. American Journal of Health-System Pharmacy. 2017;74(11 Supplement 2):S42–S46 28506976 | E2
Pedersen CA, Schneider PJ, Scheckelhoff DJ. ASHP national survey of pharmacy practice in hospital settings: dispensing and administration--2002. American Journal of Health-System Pharmacy. 2003;60(1):52–68 12533978 | E2
Perros P, Frier BM. An audit of waiting times in the diabetic outpatient clinic: role of patients’ punctuality and level of medical staffing. Diabetic Medicine. 1996;13(7):669–73 8840103 | E5
Pinsky B, Harnett J, Paulose-Ram R, Mardekian J, Samant N, Nair KV. Impact of Treatment by NCQA-Certified Physicians on Diabetes-Related Outcomes. American Health & Drug Benefits. 2011;4(7):429–38 25126367 | E1
Platek ME, Johnson J, Woolf K, Makarem N, Ompad DC. Availability of Outpatient Clinical Nutrition Services for Patients With Cancer Undergoing Treatment at Comprehensive Cancer Centers. Journal of Oncology Practice/American Society of Clinical Oncology. 2015;11(1):1–5 | E2
Potter MA, Wilson C. Applying Bureaucratic Caring Theory and the Chronic Care Model to Improve Staff and Patient Self-Efficacy. Nursing Administration Quarterly. 2017;41(4):310–320. doi:10.1097/NAQ.0000000000000256 28858999 | E1
Rabow MW, O’Riordan DL, Pantilat SZ. A statewide survey of adult and pediatric outpatient palliative care services. Journal of Palliative Medicine. 2014;17(12):1311–6 25137356 | E1
Rarick M. Treating advanced ovarian cancer within the health maintenance organization: a Kaiser Permanente approach. Seminars in Oncology. 1999;26(1 Suppl 1):52–8 | E4
Reardon JZ, Levine S, Peske G, . A comparison of outpatient cardiac and pulmonary rehabilitation patients. Journal of Cardiopulmonary Rehabilitation. 1995;15(4):277–82 8542533 | E2
Reese O, Wright C, Sandoval A, . “Establishment of an acute headache infusion clinic as an alternative for emergency department care”. Journal of the Neurological Sciences. 2021;423:117384.33714085 | E5
Reynolds L. How Do We Adequately Staff an Outpatient Oncology Unit? Clinical Journal of Oncology Nursing. 2021;25(1):104 33480872 | E7
Richter JM, Ha JB, Marx M, Campbell EJ, Pandolfi MC. A Digital Preprocedure Instruction Program for Outpatient Colonoscopy. Telemedicine Journal & E-Health. 2020;26(4):468–476 31298628 | E2
Roberts NA, Alexander K, Wyld D, Janda M. What is needed by staff to implement PROMs into routine oncology care? A qualitative study with the multi-disciplinary team. European Journal of Cancer Care. 2019;28(6):e13167 31603590 | E5
Rodriguez AL, Jackson HJ, Cloud R, Morris K, Stansel CC. Oncology Nursing Considerations when Developing Outpatient Staffing and Acuity Models. Seminars in Oncology Nursing. 2020;36(3):151018 32430212 | E4
Rogers B, Pesata B, Lee JH, Zhao J, Krieger J, Daily K. Chemotherapy education: current practices of oncology nurses counseling patients. Supportive Care in Cancer. 2021;27:27 | E2
Rosenthal MB, de Brantes FS, Sinaiko AD, Frankel M, Robbins RD, Young S. Bridges to Excellence--recognizing high-quality care: analysis of physician quality and resource use. American Journal of Managed Care. 2008;14(10):670–7 | E2
Ruane-Morris M, Thompson G, Lawton S. The reorganisation of a dermatology department. Professional Nurse. 1995;10(10):629–32 | E4
Ryan S, Hassell AB, Lewis M, Farrell A. Impact of a rheumatology expert nurse on the wellbeing of patients attending a drug monitoring clinic. Journal of Advanced Nursing. 2006;53(3):277–86 16441532 | E5
Sadler K, Bahwere P, Guerrero S, Collins S. Community-based therapeutic care in HIV-affected populations. Transactions of the Royal Society of Tropical Medicine & Hygiene. 2006;100(1):6–9 16216293 | E6
Sandberg ES, Estrada E, Jain N, . Designing and implementing an outpatient management pathway for patients with newly diagnosed insulin-dependent diabetes mellitus. Endocrinology, and Diabetes & Metabolism. 2019;2(2):e00055 | E1
Sanson-Fisher RW, Hobden BT, Carey ML, Turon HE, Waller AE, Proietto AM. The System for Patient Assessment of Cancer Experiences (SPACE): a cross-sectional study examining feasibility and acceptability. Supportive Care in Cancer. 2020;28(4):1737–1745 31292756 | E5
Sarani B, Toevs C, Mayglothling J, Kaplan LJ. The burden of the U. S. crisis in the surgical critical care workforce and workflow. American Surgeon. 2015;81(1):19–22 | E1
Sattler LA, Hunninghake JC, Sjulin TJ, . Critical Care Education and Skills Validation Course for Internal Medicine Physicians in the Military. Military Medicine. 2021;23:23 | E1
Sawicki PT, Muhlhauser I, Didjurgeit U, Berger M. Improvement of hypertension care by a structured treatment and teaching programme. Journal of Human Hypertension. 1993;7(6):571–3 8114050 | E5
Schroeder C. Nursing’s response to the crisis of access, costs, and quality in health care. Advances in Nursing Science. 1993;16(1):1–20 | E6
Schwartz LL, Raymer JM, Nash CA, Hanson IA, Muenter DT. Hypertension: role of the nurse-therapist. Mayo Clinic Proceedings. 1990;65(1):67–72 2296213 | E4
Selvig D, Sewell JL, Tuot DS, Day LW. Gastroenterologist and primary care perspectives on a post-endoscopy discharge policy: impact on clinic wait times, provider satisfaction and provider workload. BMC Health Services Research. 2018;18(1):16 29321069 | E2
Serena A, Dwyer A, Peters S, Eicher M. Feasibility of advanced practice nursing in lung cancer consultations during early treatment: A phase II study. European Journal of Oncology Nursing. 2017;29:106–114 28720257 | E5
Shaker MS, Oppenheimer J, Grayson M, . COVID-19: Pandemic Contingency Planning for the Allergy and Immunology Clinic. The Journal of Allergy & Clinical Immunology in Practice. 2020;8(5):1477–1488.e5 32224232 | E2
Shaw RJ, McDuffie JR, Hendrix CC, Edie A, Lindsey-Davis L, Williams JW Jr. Effects of Nurse-Managed Protocols in the Outpatient Management of Adults with Chronic Conditions. VA-ESP Project #09-010; 2013. | E7
Siaw MYL, Ko Y, Malone DC, . Impact of pharmacist-involved collaborative care on the clinical, humanistic and cost outcomes of high-risk patients with type 2 diabetes (IMPACT): a randomized controlled trial. Journal of Clinical Pharmacy & Therapeutics. 2017;42(4):475–482 28449205 | E1
Silvay G, Zafirova Z. Ten Years Experiences With Preoperative Evaluation Clinic for Day Admission Cardiac and Major Vascular Surgical Patients: Model for “Perioperative Anesthesia and Surgical Home”. Seminars in Cardiothoracic & Vascular Anesthesia. 2016;20(2):120–32 26620138 | E7
Silver N, Weber RS, Lozano M, . Reducing patient wait times in a head and neck cancer outpatient clinic: A pilot study. Laryngoscope. 2020;130(4):E151–E154 31070242 | E2
Skrutkowski M, Saucier A, Eades M, . Impact of a pivot nurse in oncology on patients with lung or breast cancer: symptom distress, fatigue, quality of life, and use of healthcare resources. Oncology Nursing Forum. 2008;35(6):948–54 18980926 | E5
Sly RM, O’Donnell R. Association of asthma mortality with medical specialist density. Annals of Allergy. 1992;68(4):340–4 1558330 | E2
Smith GS, Richardson A. Development of nursing documentation for use in the outpatient oncology setting. European Journal of Cancer Care. 1996;5(4):225–32 9117066 | E5
Smrke A, Younger E, Wilson R, . Telemedicine During the COVID-19 Pandemic: Impact on Care for Rare Cancers. JCO Global Oncology. 2020;6:1046–1051 32639877 | E4
Solberg LI, Maciosek MV, Sperl-Hillen JM, . Does improved access to care affect utilization and costs for patients with chronic conditions? American Journal of Managed Care. 2004;10(10):717–22 | E2
Soroka M, Crump T, Bennett A. Optometry within hospitals at the Veterans Administration. Optometry. 2005;76(11):657–60 16298319 | E5
Soteriades ES. A workplace modified duty program for employees in an oncology center. Work. 2017;56(1):157–164. doi:10.3233/WOR-162478 28128788 | E2
Sparber A. Complementary therapy in critical care settings: a review of surveys and implications for nurses. Critical Care Nursing Clinics of North America. 2003;15(3):305–312 12943136 | E10
Standiford CJ, Nolan E, Harris M, Bernstein SJ. Improving the provision of language services at an academic medical center: ensuring high-quality health communication for limited-English-proficient patients. Academic Medicine. 2009;84(12):1693–7 19940574 | E2
Steen A, Bovio Franck J. Improving clinic utilization and workload capture for clinical pharmacy specialists. American Journal of Health-System Pharmacy. 2020;77(7):552–559 32061094 | E2
Strijbos JH, Postma DS, van Altena R, Gimeno F, Koeter GH. A comparison between an outpatient hospital-based pulmonary rehabilitation program and a home-care pulmonary rehabilitation program in patients with COPD. A follow-up of 18 months. Chest. 1996;109(2):366–72 8620707 | E5
Strowd RE, Strauss L, Graham R, . Rapid Implementation of Outpatient Teleneurology in Rural Appalachia: Barriers and Disparities. Neurology Clinical Practice. 2021;11(3):232–241 34484890 | E2
Suss S, Bhuiyan N, Demirli K, Batist G. Toward Implementing Patient Flow in a Cancer Treatment Center to Reduce Patient Waiting Time and Improve Efficiency. Journal of Oncology Practice/American Society of Clinical Oncology. 2017;13(6):e530–e537 | E5
Tanaka GJ, Fujiwara J, Kramer H, Bredt AB, Wortmann M. Justification and implementation of an oncology pharmacist practitioner in an HMO setting. Hospital Pharmacy. 1985;20(8):568–9, 573–4 10272397 | E7
Tavernier SS, Beck SL, Dudley WN. Diffusion of a Distress Management Guideline into practice. Psycho-Oncology. 2013;22(10):2332–8 23712894 | E2
Tennison JM, Ngo-Huang A, Fu JB, Hill AE, Dibaj SS, Bruera E. Frequency and Characteristics of Recommendations from Interdisciplinary Outpatient Cancer Rehabilitation Monthly Team Meetings. PM&R. 2019;11(3):252–257 30010049 | E4
Thomas S, Glynne-Jones R, Chait I. Is it worth the wait? A survey of patients’ satisfaction with an oncology outpatient clinic. European Journal of Cancer Care. 1997;6(1):50–8 9238930 | E5
Thompson Stone R, Tollefson T, Epstein R, Jozefowicz RF, Mink JW. Education Research: Positive effect of scheduled faculty modeling on clerkship student bedside skills exposure and learning. Neurology. 2017;88(24):e236–e239 28607143 | E1
Thygeson NM, Wang M, O’Riordan D, Pantilat SZ. Self-Reported California Hospital Palliative Care Program Composition, Certification, and Staffing Level Are Associated with Lower End-of-Life Medicare Utilization. Journal of Palliative Medicine. 2016;19(12):1281–1287 27508981 | E1
Tierney WM, Overhage JM, Murray MD, . Can computer-generated evidence-based care suggestions enhance evidence-based management of asthma and chronic obstructive pulmonary disease? A randomized, controlled trial. Health Services Research. 2005;40(2):477–97 15762903 | E2
Tomicki S, Dieguez G, Latimer H, Cockrum P, Kim G. Real-World Cost of Care for Commercially Insured versus Medicare Patients with Metastatic Pancreatic Cancer Who Received Guideline-Recommended Therapies. American Health & Drug Benefits. 2021;14(2):70–78 34267862 | E2
Tomkins CS, Braid JJ, Williams HC. Do dermatology outpatients value a copy of the letter sent to their general practitioner? In what way and at what cost? Clinical & Experimental Dermatology. 2004;29(1):81–6 14723730 | E2
Tonna JE, Hanson HA, Cohan JN, . Balancing revenue generation with capacity generation: Case distribution, financial impact and hospital capacity changes from cancelling or resuming elective surgeries in the US during COVID-19. BMC Health Services Research, 20(1), 1–7.31888624 | E1
Vachon GC, Ezike N, Brown-Walker M, Chhay V, Pikelny I, Pendergraft TB. Improving access to diabetes care in an inner-city, community-based outpatient health center with a monthly open-access, multistation group visit program. Journal of the National Medical Association. 2007;99(12):1327–36 18229769 | E1
van Egdom LSE, Lagendijk M, van der Kemp MH, . Implementation of Value Based Breast Cancer Care. European Journal of Surgical Oncology. 2019;45(7):1163–1170 30638807 | E5
Vickery DM, Liang MH, Collis PB, . Physician extenders in walk-in clinics: a prospective evaluation of the AMOSIST program. Archives of Internal Medicine. 1975;135(5):720–5 28706 | E1
Virani SS, Akeroyd JM, Ramsey DJ, . Health Care Resource Utilization for Outpatient Cardiovascular Disease and Diabetes Care Delivery Among Advanced Practice Providers and Physician Providers in Primary Care. Population Health Management. 2018;21(3):209–216 28994631 | E1
Vortherms J, Spoden B, Wilcken J. From evidence to practice: developing an outpatient acuity-based staffing model. Clinical Journal of Oncology Nursing. 2015;19(3):332–7 26000583 | E10
Wachsberg KN, O’Leary KJ, Buck R, . Impact of Real-Time Clinical Decision Support on Blood Utilization and Outcomes in Hospitalized Patients with Solid Tumor Cancer. Joint Commission Journal on Quality & Patient Safety. 2019;45(1):57–62 30122521 | E2
Weber C, Beaulieu M, Djurdjev O, . Towards rational approaches of health care utilization in complex patients: an exploratory randomized trial comparing a novel combined clinic to multiple specialty clinics in patients with renal disease- cardiovascular disease-diabetes. Nephrology Dialysis Transplantation. 2012;27 Suppl 3:iii104–10 | E5
Weck CE, Lex KM, Lorenzl S. Telemedicine in Palliative Care: Implementation of New Technologies to Overcome Structural Challenges in the Care of Neurological Patients. Frontiers in Neurology. 2019;10:510 31178815 | E1
Weems J, Siegel RD, Bowen TN, Stinnett L, Ashley J. Embedding palliative care (pc) in a community-based cancer center: Benefits and barriers. Journal of Clinical Oncology. 2016;34(29):153–153. doi:10.1200/jco.2016.34.26_suppl.153 | E1
Weissman DE, Griffie J. The Palliative Care Consultation Service of the Medical College of Wisconsin. Journal of Pain & Symptom Management. 1994;9(7):474–9 7529812 | E1
Whitmer K, Pruemer J, Wilhelm C, McCaig L, Hester JD. Development of an outpatient oncology symptom management clinic. Clinical Journal of Oncology Nursing. 2011;15(2):175–9 21444284 | E4
Whittington MD, Ho PM, Kirsh SR, . Cost savings associated with electronic specialty consultations. American Journal of Managed Care. 2021;27(1):e16–e23 | E2
Wingo MT, Halvorsen AJ, Beckman TJ, Johnson MG, Reed DA. Associations between attending physician workload, teaching effectiveness, and patient safety. Journal of Hospital Medicine. 2016;11(3):169–73 26741703 | E2
Wood L, Richards J, Jacobs P. The role of the professional nurse in a bone marrow transplantation programme. Curationis. 1990;13(3–4):77–84 2091866 | E6
Wood S, Bisson JI. Experience of incorporating a mental health service into patient care after operations for cancers of the head and neck. British Journal of Oral & Maxillofacial Surgery. 2004;42(2):149–54 15013548 | E5
Yehia BR, Gebo KA, Hicks PB, . Structures of care in the clinics of the HIV Research Network. AIDS Patient Care & Stds. 2008;22(12):1007–13 19072107 | E2
Yu GC, Beresford R. Implementation of a chronic illness model for diabetes care in a family medicine residency program. Journal of General Internal Medicine. 2010;25 Suppl 4:S615–9 20737237 | E1
Yu J, Shah BM, Ip EJ, Chan J. A Markov model of the cost-effectiveness of pharmacist care for diabetes in prevention of cardiovascular diseases: evidence from Kaiser Permanente Northern California. Journal of Managed Care Pharmacy. 2013;19(2):102–14 23461426 | E1
Zini EM, Lanzola G, Bossi P, Quaglini S. An Environment for Guideline-based Decision Support Systems for Outpatients Monitoring. Methods of Information in Medicine. 2017;56(4):283–293 28726971 | E4

### APPENDIX C EVIDENCE TABLES

#### CHARACTERISTICS OF INCLUDED PRIMARY STUDIES

#### OUTCOME DATA OF INCLUDED PRIMARY STUDIES

#### QUALITY ASSESSMENT OF INCLUDED PRIMARY STUDIES

Cohort Studies

Uncontrolled Pre-Post Studies

Cross-sectional Studies

### APPENDIX D RESEARCH IN PROGRESS

Status | Title | Study Design | Intervention | Information Resources
Completed (July 2021) No Publication | GrandAides, a Workforce Innovation to Address Post-Acute Care | RCT | Specially trained “GrandAide” supporting outpatient post-acute care for patients discharged from the hospital with congestive heart failure. | NCT04966442

Abbreviations. RCT = randomized controlled trial

### APPENDIX E PEER REVIEWER DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | None
2 | 2 | Yes | None
3 | 3 | Yes | None
4 | 4 | Yes | None
5 | 5 | Yes | None
6 | 6 | Yes | None
Is there any indication of bias in our synthesis of the evidence?
7 | 1 | Yes – See comments below
8 | 2 | No | None
9 | 3 | No | None
10 | 4 | No | None
11 | 5 | No | None
12 | 6 | No | None
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
13 | 1 | Yes - The report focused on studies that involved staffing interventions and thus excluded many observational studies that did not involve changes in staffing practice. | Thank you for all of your thoughtful comments. We have addressed them individually below.
14 | 2 | No | None
15 | 3 | No | None
16 | 4 | No | None
17 | 5 | No | None
18 | 6 | Yes - There is more literature on use of medical scribes, including within specialty care settings such as cardiology clinics, and impacts on productivity. For example -- Clinicoecon Outcomes Res. 2013;5:399-406; Clinicoecon Outcomes Res. 2015;7:489-95. However, the review cites only one study (an RCT, still in progress). | Thanks for pointing this out. The Minneapolis ESP recently completed a systematic review of medical scribes in cardiac, orthopedic, and emergency care, and so we specifically excluded this intervention type to avoid a duplication of work. This exclusion is now noted in our Methods section.; Citation:; https://www.hsrd.research.va.gov/publications/esp/medical-scribes.cfm
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
19 | 1 | In response to a request from the VHA Office of Specialty Care Services (SCS) and Chiefs of Medicine Field Advisory Council, this Evidence Brief synthesized existing evidence on staffing models used in outpatient specialty care settings and its association with staff productivity and patient outcomes. The strengths of this Evidence Brief include the following: | None
20 | 1 | Using rigorous evidence synthesis protocols | None
21 | 1 | Reporting methodological details including data/literature search, abstraction/assessment, synthesis, and inclusion criteria | None
22 | 1 | There are several conceptual and methodological issues that warrant clarification and reconsideration in order to make the conclusion of this evidence synthesis valid and informative | Thank you for these comments. We address them individually below.
23 | 1 | There is a lack of clarity regarding the scope of this synthesis and the operationalization of staffing model(s). While the authors provided a general definition/description for the key construct – staffing models (page 6), it was not clear what aspects of staffing (e.g., staffing level, mixtures and/or proportions of different professionals, allocation of workload, tasks, and responsibilities) were used to define staffing model(s) and were considered as the team searched, assessed, and selected the primary studies. | Thank you for noting this omission. We now state our intention to examine supply-side staffing models/interventions in our Background section.
24 | 1 | The authors identified two staffing model types (implementation of new or existing staff on an existing model of care vs. establishment of a new clinic) and organized the evidence based on these types. What’s the rationale for identifying/using these two types? These two types seemingly cannot differentiate key aspects of staffing models (e.g., staffing level, mixtures and/or proportions of different professionals, allocation of workload, tasks, and responsibilities). | Thanks for noticing this. We now cite a recent Cochrane review (Butler 2019) on inpatient nurse staffing as the starting point for our example staffing model/intervention categories. We also note that no comprehensive reviews of outpatient specialty care staffing models/interventions exist, so we are providing possible categories for these models/interventions in Table 1.
25 | 1 | The report also used the term staffing interventions (sometimes interchangeably with staffing models). If an intervention is required to be included, the scope of this evidence synthesis is limited to those studies that involved changes in staffing practice, which should be clearly stated. | Thank you for highlighting this issue. We now refer to both staffing interventions and models throughout, to be inclusive of the non-interventional studies covered in this brief.
26 | 1 | Potentially as a result of the conceptual issues mentioned above, I am concerned that many of the selected primary studies included in this synthesis were not related to staffing models or staffing interventions. For example, Allison (1999) is a clinical intervention focusing on follow-up care and the intervention did not focus on staffing. Graze (2014) is about providing symptom management and Hook (2012) is about providing care navigation for cancer patients. The focus of these studies (or the nature of the interventions) was not about staffing. Consequently, it is difficult to draw conclusion about the effects of staffing from these studies because the reported outcomes/changes, especially the patient outcomes, were more likely to result from the clinical interventions, not staffing. This may lead to a significant bias in the synthesis conclusion. To mitigate this bias, I would suggest selecting only primary studies for which staffing was the main intervention or independent variable. | These are great points. We understand that the interventions or models in the studies included in this brief contained overlapping clinical and staffing components. However, in healthcare, staffing-related interventions or models that improve clinical outcomes and staffing-related interventions that improve productivity outcomes are often inextricably linked, i.e., there is usually some tradeoff between staffing-related productivity and outcomes important to patients. That said, we have now excluded Allison 1999 and Hook 2012 as neither study reported productivity outcomes. In addition, quality outcomes were moved to the productivity outcome category to better reflect their importance to productivity rather than patients. We have retained the remaining eight studies as they all involve staffing interventions/models that affect productivity and/or patient-important outcomes.
27 | 2 | The authors present a strong effort to synthesize a very challenging area to study. The paper states the potential impact of two strategies for addressing specialty care staffing: Adding staff and adding clinics. The quality of evidence available to make conclusions was low as stated by the authors, but it is helpful to see what is available. | Thank you for your comments.
28 | 2 | While within the focus of studying the impact of adding new care staff or adding new clinics has on the function of specialty care clinics the paper is thorough, there are two extremely relevant phenomenon which I suspect readers in the VHA system at this time, and likely for the forseable future, would be really interested in seeing some commentary on. COVID has completely turned clinical care in the VHA on its head as it has in the entire country. Specialty clinics are scrambling to adapt to management of patients in hybrid telemedicine structures. There is a severe staffing shortage particularly with nurses | Thanks for this! We now note these COVID-19-related staffing issues in our Future Research section.
29 | 2 | I do not believe there is any strong published literature on how best to navigate these challenges, but to the extent that the authors might have insights on how various strategies could mitigate impact of these issues, or at least acknowledge the issue in the discussion even if more generally than the specific COVID situation, I believe it would add great value to this paper. | Thank you, as noted above, we have addressed these issues in our Future Research section.
30 | 3 | 1. Page 4, line 31; Page 6, line 20: Please consider further clarifying the context by which the term “staffing model” is used. Staffing model described as matching the demand with appropriate resources (specifically human resources/staff) is accurate. Healthcare operators/administrator often use “staffing model” as an operations tool, a staffing grid, a staffing plan which defines the allocation of clinical and office staff needed on a daily basis relative to volume of patients/procedures/visits scheduled in the clinic. There are many considerations in a “staffing model” to minimizing staff shortages and maximizing staff expertise including staff workload (staff to patient panel) hours per unit of service benchmarks, acuity, staff skill mix, which were not noted at all in the article. | This is a great comment. We now note, in both the Executive Summary and the Background section, that we have focused on supply-side staffing models that involve changes in staff, types of staff, or clinic types. We did not include literature on demand-side changes that would help staffing, like reducing patient panels or accepting only less complex patients.
31 | 3 | 2. Page 6, line 31: Table 1 identifies as “intervention types” same items identified as “staffing model types” on Page 10, Lines 58-59. This is confusing | This is now fixed – thank you.
32 | 3 | 3. Page 4, line 39: define “optimal staffing methods” | This is now fixed – thank you.
33 | 3 | 4. Page 4, line 40: consider “inefficiencies or non-value added time” vs “slack” | Thank you, we have made this edit.
34 | 3 | 5. Page 7, line 50: what is a “better implemented PACT models” versus one which is not? | This is now fixed – thank you.
35 | 3 | 6. Page 9, line 49: productivity outcomes, what is the working definition of productivity? Is health care utilization a productivity measure or a patient outcome measure? Provider and staff satisfaction rates from an operations standpoint is not a productivity measure. Typical productivity measures in healthcare include volume per FTE, wRVU per 1.0 cFTE. | Thanks for catching this – we now clarify that our included outcome types (utilization; provider/staff satisfaction; cost-effectiveness) comprise our definition of “productivity outcomes.”
36 | 3 | 7. Page 10, line 58-59: “Implementation of new or existing staff on an existing model of care”, consider “addition of new staff or redefined roles of existing staff” | Thank you, we have made this edit.
37 | 3 | 8. Page 16, line 17: Consider using “advanced practice providers” vs “physician extender | We have made this edit throughout.
38 | 3 | 10. Page 17, line 43: Consider using “advanced practice providers” vs “physician extender” | We have made this edit throughout.
39 | 3 | 11. Page 20, line 25: Consider using “advanced practice providers” vs “mid-level clinicians” | We have made this edit throughout.
40 | 3 | 12. Page 20, line 59: Consider using “advanced practice providers” vs “mid-level” | We have made this edit throughout.
41 | 5 | Oncology; I reviewed the ESP brief on Specialty Care Staffing. The reviewed studies are of low quality and strong conclusions cannot be made. It does not appear this study would provide clear evidence for any particular non-physician staffing model for oncology. | Thank you for your comments.
42 | 5 | Nephrology; Concur with [X] | Thank you for your comments.
43 | 5 | Optometry; I have reviewed the attached draft. Unfortunately, there was only one study identified for optometry and it was excluded for “ineligible timing.” I don’t see any meaningful extrapolations or inferences from the other data presented in the study to validly support any conclusions for optometry. Thank you for the opportunity to review. | We agree, there is a paucity of literature in this area, thank you for your comments.
44 | 5 | Endocrinology; I concur with the findings and recommendations of the ESP specifically for Diabetes and Endocrinology but also as applicable to many specialties. | Thank you for your comments.
45 | 5 | Neurology; I have reviewed and agree with the staffing ESP report, particularly the recommendations for future research | Thank you for your comments.
46 | 6 | In this Evidence Brief, requested by the VA Office of Specialty Care Services and other partners, the authors seek to review the available evidence regarding specialty care staffing models. Specifically, they ask: (1) which staffing models for outpatient specialty care are associated with increased staff productivity and improved patient outcomes; and (2) how outpatient specialty care staffing models vary by program/clinical specialty and contextual characteristics. | Thank you for your comments.
47 | 6 | Overall, the team found only 10 studies (in 12 manuscripts) across all specialties relevant to their search, with overall low-quality evidence. Strikingly, only 2 of the 10 studies included any sort of statistical analysis. This is perhaps unsurprising because discussion of staffing models is often limited to the clinical and operations sphere, and there is a paucity of funded research in this space. The reality also is that specialties are quite distinct, and what might work well in one specialty may not work well in another. While I applaud the authors for their call for a comprehensive conceptual model of specialty care delivery to help guide future research, a ‘one-size-fits all’ model may not be feasible given inherent differences in specialty care delivery (e.g., procedural vs non-procedural specialties, short-term vs. chronic care management, etc.). Something analogous to a PACT/PCMH model may be more feasible with respect to specialty care management of patients with chronic diseases such as inflammatory bowel diseases, cirrhosis, or CHF, where in many cases the specialist serves in more of a primary care role. The real value of this review is in demonstrating the relative lack of methodologically rigorous inquiry into ways in which we might re-envision specialty care staffing models to maximize productivity (thereby improving overall Veteran access to care), patient/provider satisfaction, and patient-centered outcomes. | Thank you for your comments.
48 | 6 | A few comments to consider in revisions: I was surprised not to see more literature on use of medical scribes in the specialty care space. The authors cite a single study (an RCT still in progress), but there are at least a few more studies that were not highlighted. For example, there are several studies on use of medical scribes in cardiology clinics and impacts on productivity, which are included above. | Thanks for this. As we note above, we have specifically excluded scribes interventions in this review, as an ESP systematic review on scribes in specialty care was recently conducted.; Citation:; https://www.hsrd.research.va.gov/publications/esp/medical-scribes.cfm
49 | 6 | Training physicians and other healthcare professionals is a central part of VA’s statutory mission -- VA currently provides training for over 44,000 individual physician residents and fellows annually. Discussion of the extent to which trainee effort can be optimized within specialty care delivery models in VA to maximize trainee education while also improving overall Veteran access to care/productivity would be helpful to mention. Even if there are no current studies on this topic, it is a very relevant area to explore in future research. | Thank you for this suggestion. We did not find any studies involving staffing trainees, but we have added the topic to the Future Research section, given the importance of trainees to the VA and other teaching hospitals.
50 | 6 | The rapid expansion of virtual care and how this impacts specialty care productivity, provider and patient satisfaction, and other outcomes, is very relevant here – it seems like an oversight not to mention this at all in the discussion. Virtual care delivery did not appear to be specifically excluded in the search – if virtual care delivery models are outside the scope of the review, I would make this more explicit. | Thanks! We did not find any studies of virtual specialty care staffing models/interventions in our search, but we have mentioned this area as a topic for Future Research section in our Discussion.

### REFERENCES

1 Albert NM, Fonarow GC, Yancy CW, . Outpatient cardiology practices with advanced practice nurses and physician assistants provide similar delivery of recommended therapies (findings from IMPROVE HF). American Journal of Cardiology. 2010;105(12):1773–1779.
2 Garnett D, Hardy L, Fitzgerald E, Fisher T, Graham L, Overcash J. Nurse Case Manager: Measurement of Care Coordination Activities and Quality and Resource Use Outcomes When Caring for the Complex Patient With Hematologic Cancer. Clinical Journal of Oncology Nursing. 2020;24(1):65–74.31961839
3 Graze L, Brady-Copertino C, Varner A, Stiver WS. The development of a nursing assessment and symptom management clinic. Clinical Journal of Oncology Nursing. 2014;18 Suppl:12–16.25252985
4 Huang YL, Bryce AH, Culbertson T, . Alternative Outpatient Chemotherapy Scheduling Method to Improve Patient Service Quality and Nurse Satisfaction. Journal of oncology practice/American Society of Clinical Oncology. 2018;14(2):e82–e91.
5 Reese O, Wright C, Sandoval A, . “Establishment of an acute headache infusion clinic as an alternative for emergency department care”. Journal of the Neurological Sciences. 2021;423:117384.33714085
6 Ross SC. An option for improving access to outpatient general neurology. Neurology Clinical Practice. 2014;4(5):435–440.29443242
7 Ruder AD, Smith DL, Madsen MT, Kass FH, 3rd. Is there a benefit to having a clinical oncology pharmacist on staff at a community oncology clinic? Journal of Oncology Pharmacy Practice. 2011;17(4):425–432.21248174
8 Smith GO, Jr. The role of physician assistants in improving renal care. Nephrology News & Issues. 2004;18(5):51–56.
9 Fonarow GC, Albert NM, Curtis AB, . Improving evidence-based care for heart failure in outpatient cardiology practices: primary results of the Registry to Improve the Use of Evidence-Based Heart Failure Therapies in the Outpatient Setting (IMPROVE HF). In. Circulation. Vol 1222010:585–596.
10 Fessele K, Yendro S, Mallory G. Setting the bar: developing quality measures and education programs to define evidence-based, patient-centered, high-quality care. Clinical Journal of Oncology Nursing. 2014;18.