# Evidence Brief: Coronary Computed Tomography Angiography with Fractional Flow Reserve in Noninvasive Diagnosis of Coronary Artery Disease

## PREFACE

The VA Evidence Synthesis Program (ESP) was established in 2007 to provide timely and accurate syntheses of targeted healthcare topics of importance to clinicians, managers, and policymakers as they work to improve the health and healthcare of Veterans. These reports help:

- Develop clinical policies informed by evidence;
- Implement effective services to improve patient outcomes and to support VA clinical practice guidelines and performance measures; and
- Set the direction for future research to address gaps in clinical knowledge.

The program is composed of three ESP Centers across the US and a Coordinating Center located in Portland, Oregon. Center Directors are VA clinicians and recognized leaders in the field of evidence synthesis with close ties to the AHRQ Evidence-based Practice Center Program. The Coordinating Center was created to manage program operations, ensure methodological consistency and quality of products, and interface with stakeholders. To ensure responsiveness to the needs of decision-makers, the program is governed by a Steering Committee composed of health system leadership and researchers. The program solicits nominations for review topics several times a year via the program website (https://www.hsrd.research.va.gov/publications/esp/TopicNomination.cfm).

Comments on this evidence report are welcome and can be sent to Nicole Floyd, Deputy Director, ESP Coordinating Center at Nicole.Floyd@va.gov.

## EXECUTIVE SUMMARY

#### Background

The Evidence Synthesis Program is responding to a request from the VA Health Services Research and Development Service (HSR&D) for an updated evidence brief on the diagnostic, therapeutic, and clinical impact of CCTA with FFR_CT_ technologies for the diagnosis of CAD. Findings from this review will be used to inform use of FFR_CT_ technologies in the VHA.

#### Methods

To identify studies, we searched MEDLINE®, Cochrane Database of Systematic Reviews, Cochrane Central Register of Controlled Trials, and other sources up to February 2021. We used prespecified criteria for study selection, data abstraction, and rating internal validity and strength of the evidence. See our PROSPERO protocol for our full methods.

#### Key Findings

- Diagnostic accuracy
  - Previous findings: Compared to coronary computed tomography angiography (CCTA) alone, HeartFlow FFR_CT_ analysis (HeartFlow) likely has good diagnostic accuracy, and a higher specificity and similar sensitivity for identifying obstructive coronary disease when using a reference standard of invasive fractional flow reserve.
  - New evidence: Several new studies agree with these findings.
- Patients referred directly for invasive coronary angiography (ICA)
  - Previous findings: HeartFlow reduced ICA use in community settings, but the applicability to VA settings is low.
  - New evidence: None
- Patients with suspected coronary disease referred for noninvasive testing
  - Previous findings: In community settings, HeartFlow increased ICA use compared to other noninvasive strategies.
  - New evidence: None
- Patients with suspected coronary disease referred for CCTA
  - Previous findings: None
  - New evidence: A single new study examined ICA use in patients with suspected coronary disease undergoing CCTA, but findings are limited by major methodological concerns.
- Effect on cardiac events
  - Previous findings: In the short term (90 days to 1 year), rates of cardiac events were similar in those receiving HeartFlow and those receiving other diagnostic strategies, and in patients whose clinical management plans changed after use of HeartFlow compared to those whose clinical management plans did not change with use of HeartFlow.
  - New evidence: Several new studies agree with these findings.
- Future research
  - Research in VA settings and comparing HeartFlow to specific noninvasive strategies is needed to determine the potential impact of HeartFlow within the VA.

Noninvasive diagnostic strategies for evaluation of patients with stable chest pain include functional imaging (single-photon emission CT, positron emission tomography scanning, pharmacologic echocardiography, etc), and anatomic imaging with coronary computed tomography angiography (CCTA). CCTA generally has good diagnostic accuracy, but it lacks the ability to assess the functional significance of coronary artery disease (CAD). Fractional flow reserve (FFR) measured invasively during coronary angiography is considered the gold standard for detecting hemodynamically significant CAD. Noninvasive techniques have been developed to estimate FFR from CCTA images (FFR_CT_) with the aim of gaining both functional and anatomical information on the extent of coronary artery narrowing and the impact on blood flow.

HeartFlow, currently the only commercially available and FDA-cleared FFR_CT_ technology, uses computer modeling and CCTA images to produce color-coded maps showing functionally significant coronary artery narrowing.

In 2019, the Evidence Synthesis Program (ESP) prepared a white paper report synthesizing the evidence on the diagnostic accuracy and therapeutic and clinical impact of FFR_CT_ technologies for the diagnosis of CAD. Three clinical scenarios for the potential use of HeartFlow were identified from the literature, and, for each scenario, important gaps in the evidence were described (Table ES-1). Briefly, we found that in community settings, HeartFlow FFR_CT_ analysis reduced the use of ICA among patients referred directly to ICA. This evidence was not applicable to the VA, where practices regarding direct referral to ICA and use of CCTA differ from those in community settings. We did not find compelling evidence that using CCTA plus HeartFlow would reduce ICA use in patients who undergo other types of noninvasive testing for suspected coronary disease.

Table ES-1 Evidence Gaps Identified in 2019 ESP Report on FFR_CT_ Technologies

Outcome | | Evidence Gaps Identified in 2019 ESP Report
Diagnostic Accuracy | | No evidence in VA.
ICA Use | Clinical Scenario 1: HeartFlow use in patients directly referred to ICA | Evidence has low applicability to VA settings because of differences in ICA referral practices and use of CCTA.
ICA Use | Clinical Scenario 2: HeartFlow use as a substitute for other noninvasive testing | No direct comparison to other noninvasive strategies. Evidence has low applicability to VA settings because of differences in ICA referral practices and use of CCTA.
ICA Use | Clinical Scenario 3: HeartFlow use in patients referred for CCTA | No evidence.
Clinical Outcomes | | No evidence on long-term clinical outcomes. No evidence in VA settings.

Abbreviations: ESP=Evidence Synthesis Program, ICA=Invasive coronary angiography, VA=Veterans Administration.

The goal of the present report was to provide an updated synthesis of the evidence on the use of HeartFlow for noninvasive diagnosis of CAD, focusing on evidence that is most relevant to the VA and most applicable to evidence gaps identified in the 2019 ESP review. Based on our updated summary of findings (Table ES-2), we found that new evidence has not resolved the evidence gaps identified in the 2019 ESP report:

- Diagnostic accuracy: New evidence on the diagnostic accuracy of HeartFlow agreed with findings from the 2019 ESP report, confirming that HeartFlow likely has good diagnostic accuracy and a higher specificity and similar sensitivity for identifying obstructive coronary disease to that of CCTA alone. No studies were in VA settings.
- ICA Use:
  - Clinical Scenario 1: No new evidence examined HeartFlow use in patients planned to be directly referred to ICA.
  - Clinical Scenario 2: No new evidence examined HeartFlow use as a substitute for other noninvasive testing.
  - Clinical Scenario 3: A single new study compared HeartFlow use in patients undergoing CCTA alone or HeartFlow. However, this study had severe methodological limitations. Although the specificity of HeartFlow is improved over CCTA alone, the impact on downstream utilization of ICA needs to be verified.
- Clinical Outcomes: New evidence supports previous findings that short-term (90 days to 1 year) rates of cardiac events are similar in those receiving HeartFlow and those receiving other diagnostic strategies, and in patients whose clinical management plans changed after use of HeartFlow compared to those whose clinical management plans did not change with use of HeartFlow. A single new study on longer-term (~5 years) clinical outcomes reported rates of major adverse cardiac events but did not compare clinical events between those receiving HeartFlow and other diagnostic strategies.

Table ES-2 Updated Summary of Findings

Outcome | Evidence | Summary of Findings
Diagnostic Accuracy | 3 SRs^1–3^ (1 new); 7 primary studies^4–10^ (5 new) | Several systematic reviews with few study limitations and precise estimates consistently reported good diagnostic accuracy for HeartFlow (AUC range 0.87 to 0.89). Several primary studies published since the systematic reviews with moderate study limitations generally supported these findings but had a broader range of estimates (AUC range 0.82 to 0.94).; Moderate SOE
ICA Use | 1 cohort^11^ (0 new) | Scenario 1: Compared to direct referral to ICA; HeartFlow reduced ICA use compared to planned ICA in a single cohort directly comparing HeartFlow to planned ICA.; Low SOE (moderate study limitations and imprecise estimates)
ICA Use | 2 cohorts^11,12^ (0 new) | Scenario 2: Compared to other noninvasive strategies; HeartFlow may increase ICA use compared to other noninvasive testing strategies. Two cohorts reported conflicting findings.; Low SOE (moderate study limitations, imprecise estimates, inconsistent results, and limited comparisons to specific noninvasive testing strategies)
ICA Use | 1 cohort^13^ (1 new) | Scenario 3: Compared to CCTA alone; It is unclear whether HeartFlow reduces ICA use compared to CCTA alone. A single cohort with severe study limitations and unknown precision directly compared HeartFlow to CCTA alone.; Insufficient SOE
Change in Clinical Management | 3 cohorts^14–16^ (1 new); 6 case series^17–23^ (3 new) | Scenario 3: Compared to CCTA alone; HeartFlow changed treatment plans in 28% to 67% of patients compared to CCTA alone (48% to 91% had ICA cancellation) in several cohorts and case series with moderate study limitations and mostly precise estimates reporting a wide range of estimates of changes in treatment plans.; Moderate SOE
Adverse Clinical Events | 3 cohorts^11,15,16,24^ (0 new); 4 case series^19,21,22,25–28^ (2 new) | MACE events were low (<2%) at 90 days to 1 year in patients receiving HeartFlow and were similar in patients receiving HeartFlow or other diagnostic strategies in several cohorts and case series with generally consistent findings.; Low SOE (moderate study limitations, unknown precision, and sparse data)

Abbreviations. AUC=area under the curve, CCTA=coronary computed tomography angiography, CI=confidence interval, ICA=invasive coronary angiography, MACE=major adverse cardiac events, SOE=strength of evidence, SR=systematic review.

Data from the VA Corporate Data Warehouse show that use of CCTA within the VA remains relatively low (~2000 performed each year from 2018 to 2020), suggesting that regular use of HeartFlow for all patients referred for CCTA within the VA may have a low impact on ICA use. However, targeted use of HeartFlow in facilities with a high volume of CCTA use in specific clinical scenarios may have the potential to reduce unnecessary use of coronary angiography. CCTA use, a prerequisite for using FFR_CT_ analysis, is unlikely to change in the VA unless clinicians are persuaded by direct evidence that a CCTA-based strategy is preferable to other noninvasive strategies. Challenges in integrating HeartFlow into current clinical pathways and the need for access to and training for CCTA remain barriers for the use of HeartFlow within the VA. Population (demographics, cardiac risk factors, etc) and clinical (types of noninvasive strategies used, access to CCTA and/or ICA, etc) characteristics may differ between the VA and those in trials of HeartFlow, and research in VA settings is needed to determine the potential impact of HeartFlow within the VA. Controlled studies of ICA rates in patients with suspected coronary disease receiving CCTA or other noninvasive strategies and comparing HeartFlow to specific noninvasive strategies are needed.

## PURPOSE

The ESP Coordinating Center (ESP CC) is responding to a request from the VA Health Services Research and Development Service (HSR&D) for an updated evidence brief on the diagnostic, therapeutic, and clinical impact of coronary computed tomography angiography (CCTA) with fractional flow reserve (FFR_CT_) technologies for the diagnosis of coronary artery disease (CAD). Findings from this review will be used to inform use of HeartFlow FFR_CT_ analysis in the Veterans Health Administration (VHA).

## BACKGROUND

A more detailed background is provided in the 2019 ESP report on FFR_CT_ technologies.^29^

### CCTA TECHNOLOGIES

Patients with chest pain and low to intermediate pre-test probability of stable CAD are typically evaluated noninvasively, commonly with standard exercise electrocardiogram (ECG) for patients who are able to exercise. For patients who cannot exercise or have an uninterpretable resting ECG, noninvasive functional imaging options include pharmacologic stress plus nuclear imaging (single-photon emission CT (SPECT) or positron emission tomography (PET) scanning) or pharmacologic echocardiography.^30^ Noninvasive anatomical imaging with CCTA is another option for patients who cannot exercise and who have intermediate to high probability of significant coronary artery disease.^31,32^

CCTA generally has a high sensitivity for functionally significant coronary lesions (range 86% to 95% in recent meta-analyses^2,3,33^), with few false negatives. However, the specificity is 61% to 79%,^2,3,33^ and the potential for false positives often leads to the use of invasive coronary angiography (ICA) to exclude the presence of significant CAD and assess its functional significance. The gold standard for detecting hemodynamically significant CAD is fractional flow reserve (FFR), or the fraction of maximum blood flow in a restricted artery.^34^ Measurement of FFR requires an invasive procedure to place a pressure wire to calculate pressure and blood flow information,^35,36^ and novel techniques have emerged to calculate FFR noninvasively from CCTA images (FFR_CT_). The aim of FFR_CT_ is to gain both functional and anatomical information on the extent of coronary artery narrowing and the impact on blood flow.^36,37^

#### HeartFlow FFR_CT_ Analysis

HeartFlow uses computer modeling and CCTA images to produce noninvasive 3-dimensional FFR models, and is the only commercially available and FDA-cleared FFR_CT_ technology.^38,39^ Physicians or health systems can send high-quality (ie, artifact-free) CCTA images to HeartFlow, Inc. (Redwood City, California), where the images are used to produce a color-coded map of the coronary arteries with estimated FFR values. The map shows the physiological impact of coronary artery narrowing on blood flow, and physicians can manipulate the model to examine each vessel and analyze the location and severity of lesions. HeartFlow also offers an interactive tool (“HeartFlow Planner”), which can model various clinical scenarios and treatment plans based on the patient-specific HeartFlow model.^40^

A recent Health Technology Assessment by the ECRI Institute reported that evidence on the diagnostic accuracy and therapeutic and clinical impact is somewhat favorable for the use of HeartFlow for guiding treatment in patients with suspected CAD.^41^ Recent narrative reviews generally agree that HeartFlow offers advantages in noninvasive diagnosis of CAD with improved diagnostic accuracy and reductions in ICA use in specific clinical situations.^42,43^ Additionally, guidance from the National Institute for Health and Care Excellence (NICE) in the UK recommends using HeartFlow for patients with stable recent onset chest pain who are offered CCTA as a part of the clinical pathway.^44^ In the US, many major medical centers use HeartFlow, and the Centers for Medicare and Medicaid Services (CMS) and several commercial payers cover the use of HeartFlow in specific clinical situations.^45,46^ The VA does not currently have guidelines or coverage policies regarding the use of HeartFlow FFR_CT_ analysis.

#### Other FFR_CT_ Technologies

Numerous other FFR_CT_ algorithms exist, including Siemens Healthcare cFFR, Canon Medical Systems CT-FFR, and independent, locally developed machine learning and reduced order modeling techniques.^2,3,38^ Unlike HeartFlow, these technologies can be used within individual clinics, hospitals, or research environments without the need for analyses by an outside entity. However, none are commercially available or FDA cleared at the time of this report.

### 2019 ESP CC REPORT ON FFR_CT_ TECHNOLOGIES

In 2019, the ESP prepared a white paper report synthesizing the evidence on the diagnostic accuracy and therapeutic and clinical impact of FFR_CT_ technologies for the diagnosis of CAD.^29^ Key findings and evidence gaps from this report are summarized in Table 1. For diagnostic accuracy outcomes, 2 meta-analyses and several subsequent primary studies generally agreed that HeartFlow is more specific than CCTA alone, using a reference standard of invasive FFR. Studies examining reductions in ICA use fell into 3 clinical scenarios for the potential use of HeartFlow: (1) in patients who are planned to be directly referred to ICA in lieu of noninvasive evaluation, (2) as a substitute for other noninvasive testing, and (3) as a part of the clinical pathway for patients referred for CCTA. The PLATFORM trial^11^ reported that HeartFlow reduced the use of coronary angiography in patients planned to be directly referred to ICA (scenario 1), but led to a higher rate of coronary angiography in patients planned for noninvasive testing (scenario 2). No studies reported on ICA use as a part of the clinical pathway for patients referred for CCTA (scenario 3). Evidence on the impact of the use of HeartFlow on clinical outcomes was limited to short-term (90-day to 1-year) findings.

As no trials were conducted in VA settings – and because the utility of HeartFlow depends on clinical practices and frequency of use of CCTA, the characteristics of patients who undergo CCTA, and on how decisions about ICA are made within a particular setting – the previous report concluded that additional trials were necessary to understand the potential impact of HeartFlow use within the VA. Additionally, further data on the long-term impact of HeartFlow on clinical outcomes were needed. Finally, existing evidence did not justify substituting CCTA with FFR_CT_ for other noninvasive tests, and direct evidence was needed about how HeartFlow compares to other noninvasive diagnostic tests, specifically those widely used in the VA.

Table 1 Summary of Findings and Evidence Gaps in 2019 ESP Report

2019 ESP Report Summary of Select Key Findings | Diagnostic accuracy: In patients with suspected coronary disease, CCTA with HeartFlow is more specific than CCTA alone using the reference standard of invasive FFR. The additional functional information provided by HeartFlow more accurately detects patients without functionally significant obstructive CAD.
2019 ESP Report Summary of Select Key Findings | Reduction in ICA use:; - Clinical Scenario 1: In patients planned to be directly referred to ICA: HeartFlow led to a lower rate of coronary angiography in patients planned to be directly referred to ICA.; - Clinical Scenario 2: As a substitute for other noninvasive testing: HeartFlow led to a higher rate of ICA use when used as a substitute for planned noninvasive cardiovascular testing.; - Clinical Scenario 3: In patients referred for CCTA: No evidence on the impact on ICA use.
2019 ESP Report Summary of Select Key Findings | Clinical outcomes: Rates of MACE outcomes were low and were similar between patients using HeartFlow and other diagnostic strategies. The effect on longer-term MACE outcomes is uncertain.
Evidence Gaps for VA | Reduction in ICA use: Evidence is needed in a VA setting demonstrating a reduction in ICA with HeartFlow compared to current VA diagnostic strategies.
Evidence Gaps for VA | Clinical outcomes: Evidence is needed demonstrating the impact of HeartFlow compared to current VA diagnostic strategies on longer-term clinical and MACE outcomes.

Abbreviations: CCTA=coronary computed tomography angiography, FFR=fractional flow reserve, ICA=invasive coronary angiography, MACE=major adverse cardiovascular events.

The goal of the present report was to provide an updated synthesis of the evidence on the use of HeartFlow for noninvasive diagnosis of CAD, focusing on evidence that is most relevant to the VA and most applicable to evidence gaps identified in the 2019 ESP review.

## METHODS

### PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; CRD42021243717).

### KEY QUESTIONS

Key Question 1 What is the diagnostic accuracy of HeartFlow FFR_CT_ analysis for diagnosing CAD?
Key Question 2 What is the diagnostic and therapeutic impact of HeartFlow FFR_CT_ analysis in guiding the diagnosis and treatment of CAD?
Key Question 3 What is the impact of the use of HeartFlow FFR_CT_ analysis on clinical outcomes and cost in the diagnosis and treatment of CAD?

### ELIGIBILITY CRITERIA

The ESP included studies that met the following criteria:

- [underlined: P]opulation: Adult candidates for non-invasive evaluation for coronary disease or invasive coronary angiography
- [underlined: I]ntervention: HeartFlow FFR_CT_ analysis
- [underlined: C]omparator: Any other diagnostic strategy for CAD (coronary computed tomography angiography [CCTA], exercise electrocardiogram [ECG], exercise or pharmacologic stress echocardiography, exercise or pharmacologic cardiac nuclear imaging with single-photon emission computed tomography [SPECT], positron emission tomography [PET], cardiovascular magnetic resonance [CMR], etc)
- [underlined: O]utcomes: Diagnostic accuracy (sensitivity, specificity, etc), use of invasive coronary angiography, changes in clinical or therapeutic management of patients, cost, major adverse cardiac events (MACE), other adverse clinical events (mortality, myocardial infarction, etc)
- [underlined: T]iming: Any
- [underlined: S]etting: Any
- [underlined: S]tudy design: Any, but we may prioritize articles using a best evidence approach to accommodate the timeline.

### DATA SOURCES AND SEARCHES

To identify recent literature on diagnostic accuracy and clinical effectiveness, we searched MEDLINE, Cochrane Database of Systematic Reviews, and Cochrane Central Register of Controlled Trials using terms for HeartFlow, fractional flow reserve, and computed tomography angiography published since 2019, the end search date of our recent evidence review^29^ (see Appendix A in supplemental materials for complete search strategies). The search was limited to publications involving human subjects available in the English language. Additional information was gathered by cross-checking reference lists, searching citing articles, reviewing FDA documents, searching for ongoing clinical trials, and consulting with content experts. One investigator first reviewed all titles, abstracts, and full-text articles, with a second investigator checking. All disagreements were resolved by consensus or discussion with a third reviewer.

### DATA ABSTRACTION AND ASSESSMENT

We abstracted data on study design, population characteristics, diagnostic accuracy, and therapeutic and clinical impact outcomes from all included studies. All data abstraction was first completed by 1 reviewer then checked by another reviewer. We used predefined criteria to critically appraise all included studies, including the Cochrane ROBIS tool for systematic reviews,^47^ the QUADAS-2 tool for diagnostic accuracy studies,^48^ the Cochrane ROBINS-I tool for cohort studies,^49^ and the tool developed by Murad et al^50^ for case series. For noncomparative studies assessing changes in clinical management plans and real-world implications of utilizing HeartFlow, we used ROBINS-I to identify strengths and deficiencies of the studies. All included studies were appraised independently by 2 reviewers. Disagreements were resolved by consensus or discussion with a third reviewer.

We graded the strength of the evidence based on the AHRQ Methods Guide for Comparative Effectiveness Reviews.^51^ This approach provides a rating of confidence in reported findings based on study methodology (design, quality, and risk of bias), consistency (whether effects are in the same direction and have a consistent magnitude), directness (whether assessed outcomes are clinically important to patients and providers), and precision (narrowness of the range of confidence intervals). For this review, we applied the following general algorithm: high strength evidence consisted of multiple studies with low study limitations, direct outcomes, narrow confidence intervals, and consistent findings; moderate strength evidence consisted of multiple studies with low to moderate study limitations, direct outcomes, and consistent findings; low strength evidence consisted of single or multiple studies with moderate study limitations and wide confidence intervals and/or inconsistent findings; and insufficient evidence consisted of a single study with moderate or high study limitations, or no available trials. Strength of evidence ratings were applied to primary outcomes for all included studies.

### SYNTHESIS

We synthesized available evidence narratively by outcome and clinical scenario. To improve our interpretation of the applicability of findings to current VA practice patterns, we retrieved data from the VA Corporate Data Warehouse (CDW) on the number of patients receiving CCTA tests and the number of these patients who went on to ICA within 90 days of CCTA testing. We accessed data through the VA Informatics and Computing Infrastructure.^52^ To better match VA patients with participants in trials of HeartFlow, we limited the data to patients without acute coronary syndrome, a diagnosis of CAD, a history of previous revascularization within the year prior to CCTA, or a history of ICA.^11^ CDW codes used are available upon request. Finally, a technical expert panel (TEP) provided input on the clinical relevance of evidence and important considerations for use of HeartFlow within the VA.

## RESULTS

### LITERATURE FLOW

The literature flow diagram (Figure 1) summarizes the results of the study selection process (see Appendix B in supplemental materials for full list of excluded studies).

Figure 1 Literature Flow Chart

Abbreviations. CCRCT=Cochrane Central Register of Controlled Trials, CDSR=Cochrane Database of Systematic Reviews, SR=Systematic Review.

### LITERATURE OVERVIEW

Among 740 potentially relevant citations, we included 3 systematic reviews^1–3^ (1 new since 2019 ESP report) and 7 primary studies^4–10^ (5 new since 2019 ESP report) on diagnostic accuracy, and 14 studies (in 23 publications)^11–28,53–57^ reporting diagnostic or therapeutic impact or clinical or cost outcomes (7 new since 2019 ESP report) (Table 2, see Appendix C in supplemental materials for full study details). We also identified 6 ongoing studies examining the use of HeartFlow. Most of these studies examine diagnostic accuracy, but a few examine clinical outcomes, including 1 ongoing trial comparing clinical and cost outcomes of using CCTA with selected FFR_CT_ or usual care (see Appendix D in supplemental materials for list of ongoing studies).

#### Diagnostic Accuracy

One meta-analysis^1^ and 5 primary studies^4,5,7,9,10^ published since the 2019 ESP report examined the diagnostic accuracy of HeartFlow. The new meta-analysis included 1 primary study not included in either of the previously included meta-analyses. Diagnostic accuracy of HeartFlow was assessed in patients with suspected CAD undergoing CCTA, often along with other noninvasive testing (ie, SPECT, PET), compared to the reference standard of ICA with invasive FFR measurement. All studies used a cut-off value of FFR ≤ 0.80 to identify functionally significant CAD. Sample sizes of included studies ranged from 51 to 208 patients, with the exception of 1 study that included nearly 1500 patients^5^ (although it is unclear how many patients in this study were included in the diagnostic accuracy analysis). The applicability of this evidence to patients with low to intermediate pre-test risk of CAD is unclear as several studies excluded patients with low to intermediate risk of CAD^8,9^ or limited analyses to those with known CAD^10^ or at least 30% stenosis on ICA.^4^ Findings of several studies may have been impacted by unclear blinding of HeartFlow and/or invasive FFR values, and by exclusion of patients from analyses due to unreadable CCTA scans or lack of invasive FFR data.

#### Therapeutic and Clinical Outcomes

Seven studies published since the 2019 ESP report examined therapeutic or clinical outcomes of HeartFlow.^13,14,17,20,23,26,28^ Most were noncomparative studies, reporting on real-world clinical experiences and changes in clinical management plans in patients with an intermediate risk of CAD undergoing CCTA; none were RCTs (Table 2). Several new sub-analyses of the Assessing Diagnostic Value of Noninvasive FFR_CT_ in Coronary Care (ADVANCE) registry, an international registry of over 5,000 patients with suspected CAD (> 30% stenosis on CCTA) undergoing HeartFlow FFR_CT_ analysis from 2015 to 2017, examined outcomes by various demographic factors (age, gender, etc).^19,22,25,27,53–55^ All but 2 studies included at least 200 patients (range: 75 to 5,083). Studies frequently had important methodological limitations, including lack of concurrent control groups, unclear methods for selecting patients into the study, baseline differences between comparison groups, lack of or unclear methods for statistical adjustment, and exclusion of patients with missing FFR_CT_ data.

Table 2 Characteristics of HeartFlow Studies with Therapeutic and/or Clinical Outcomes

Author, Year Study Type | Sample Size Follow-Up | Population | Patient Demographics | Cardiac Risk Factors Pre-test Probability^a^ | Comparator | Outcomes Assessed
ADVANCE Registry
Anastasius, 2020^25^; Intl registry | N=4553; 1 year | Clinically stable symptomatic patients diagnosed with CAD by CCTA with FFRCT result | Age: 66.1; Male: 66.5%; Race: NR | Diabetes: 22.1%; Hypertension: 60.1%; Hyperlipidemia: 58.5%; Risk score: 51.6% | None | ICA use, MACE
Fairbairn, 2020^53^; Patel, 2020^27^; Intl registry | N=4737; 90 days; 1 year | Clinically stable symptomatic patients diagnosed with CAD by CCTA with FFRCT result | Age: 66.1; Male: 66.2%; Race NR | Diabetes: 21.9%; Hypertension: 59.8%; Hyperlipidemia: 58.1%; Risk score: 51.6% | None | ICA use, MACE
Fairbairn, 2018^19^; Nous, 2021^54^; Intl registry | N=5083; 90 days; 1 year | Clinically stable symptomatic patients diagnosed with CAD by CCTA | Age: 66; Male: 65.9%; Race NR | Diabetes: 22.3%; Hypertension: 59.9%; Hyperlipidemia: 58.2%; Risk score: 51.3% | None | ICA use, change in treatment plan, MACE
Pontone, 2019^55^; Intl registry | N=2778; NR | Clinically stable symptomatic patients diagnosed with CAD by CCTA with FFRCT result | Age: 66; Male: 66%; Race NR | Diabetes: 22%; History of smoking: 61%; Hyperlipidemia: 61%; Risk score: NR | None | FFRCT rejection rate
Shiono, 2019^22^; Intl registry | N=1829; 90 days | Clinically stable symptomatic patients diagnosed with CAD by CCTA in Japan | Age: 69.4; Male: 65.4%; Race: NR | Diabetes: 32.5%; Hypertension: 60.2%; Hyperlipidemia: 60.2%; Risk score: 55% | None | ICA use, change in treatment plan, MACE
PLATFORM
Colleran, 2017^56^; Prospective cohort | N=116; 1 year | Symptomatic adult patients with intermediate likelihood of obstructive CAD, without known CAD in Germany | Age: 59.9; Male: 57.7%; 1.7% racial/ethnic minority | Diabetes: 13.0%; Hypertension: 62.8%; Dyslipidemia: 21.5%; Risk score: 50.1% | Originally planned testing: ICA | ICA use, cost, quality of life
Douglas, 2015^11^; Douglas, 2016^24^; Hlatky, 2015^57^; Prospective cohort | N=584; 90 days; 1 year | Symptomatic adult patients with intermediate likelihood of obstructive CAD, without known CAD | Age: 60.9; Male: 60.4%; 1.5% racial/ethnic minority | Diabetes: 13.7%; Hypertension: 54.3%; Dyslipidemia: 34.8%; Risk score: 49% | Originally planned testing ("usual care"): non-invasive testing ICA | ICA use, MACE, cost, quality of life scores
Other Studies
Andreini, 2019 ^14^; Prospective cohort | N=223; NR | Patients with CAD diagnosed with ICA or CCTA and candidates for PCI or CABG | Age: 67.6; Male: 84.3%; Race: NR | Diabetes: 37.7%; Hypertension: 74.9%; Hyperlipidemia: 70%; Risk score: NR | CCTA or ICA | Treatment decision change between PCI and CABG
Baggiano, 2020 ^17^; Retrospective analysis ^b^ | N=291; NR | Symptomatic patients scheduled for ICA + invasive FFR | Age: 65; Male: 76%; Race: NR | Diabetes: 19%; Hypertension: 74%; Risk score: 65% | None | Reclassification rate, clinical plan agreement with actual patient management
Curzen, 2016^18^; Retrospective analysis^c^ | N=200; NR | Patients with suspected stable CAD and at least one stenosis (30–90%) on CCTA undergoing nonemergent ICA | NR | NR | None | Change in clinical management plan,
Fares, 2019 ^20^; Case series | N=207; NR | Patients with suspected CAD referred for FFRCT | Age: 69.5; Male: 46.4%; Race: 28.5%; African American, 66.4% White | Diabetes: 21.5%; Hypertension: 67.7%; Dyslipidemia: 66.7%; Risk score: NR | None | Change in clinical recommendation
Ihdayhid, 2019 ^26^; Case series | N=206; 4.7 yrs (median) | Patients with suspected stable CAD and at least 1 stenosis (30–90%) on CCTA undergoing nonemergent ICA with FFRCT | Age: 64; Male: 64.1%; Race: 68.4%; White, 31.6% Asian | Diabetes: 22.8%; Hypertension: 65.5%; Hypercholesterolemia: 81.1%; Risk score: 54.2% | None | MACE, composite outcome (death, MI and any revascularization)
Jang, 2016^21^; Case series | N=75; NR | Patients undergoing CCTA and referred for ICA | Age: 60; Male: 75%; Race NR | NR | None | Clinical management plan changed, MACE
Jensen, 2018^15^; Prospective cohort | N=774; 90 days | Symptomatic patients referred to non-emergent ICA or CCTA on suspicion of stable CAD | Age: 59; Male: 52%; Race: NR | Diabetes: 9%; Hypertension: 37%; Hyperlipidemia: 32%; Risk score: 40% | CCTA alone (planned ICA or planned CCTA) | ICA cancellation, MACE
Norgaard, 2020 ^28^; Case series | N=975; 2.2 yrs (median) | Patients with suspected chronic coronary syndrome and stenosis (30–70%) on CCTA | Age: 61.9; Male: 59.1%; Race NR | Diabetes: 12.0%; Hypertension: 45.4%; Hyperlipidemia: 37.7%; Risk score: 44.8% | None | Composite outcome (death, MI, hospitalization, revascularization)
Norgaard, 2017^16^ (Clinical use); Retrospective cohort | N=1248; 6 to 8 months | Symptomatic patients with suspected CAD undergoing CCTA | Age: 57; Male: 47%; Race: NR | Diabetes: 10%; Hypertension: 34%; Hyperlipidemia: 29%; Risk score: 34% | CCTA alone | ICA cancellation, MACE
Norgaard, 2017^12^ (Myocardial perfusion); Retrospective cohort | N=3523; 3 months | Symptomatic patients with suspected CAD undergoing CCTA | Age: 56.5; Male: 47.0%; Race: NR | Diabetes: 7.9%; Hypertension: 35.4%; Hyperlipidemia: 30.5%; Risk score: 33.2% | MPI (Period 1) FFRCT (Period 2-3) | ICA use
Rabbat, 2020 ^13^; Prospective cohort | N=431; NR | Patients with suspected CAD referred for CCTA | Age: 58.9; Male: 48.4%; Race: NR | Diabetes: 16.7%; Hypertension: 59.5%; Hyperlipidemia: 63%; Intermediate risk: 89.2% | CCTA alone | ICA use
Van Belle, 2021 ^23^; Case series | N=101; NR | Patients with at least 1 stenosis ≥ 40% with FFRCT and undergoing ICA | NR | NR | ICA | PCI strategy change

Notes. Boldface indicates new evidence since 2019 ESP report.

a Diamond-Forrester risk score,

b Analysis of PERFECTION diagnostic accuracy study,

c Analysis of NXT diagnostic accuracy study.

Abbreviations. CABG=coronary artery bypass graft, CAD=coronary artery disease, CCTA=coronary computed tomography angiography, FFRCT=fractional flow reserve using computed tomography, ICA=invasive coronary angiography, Intl=international, MACE=major adverse cardiovascular event, MI=myocardial infarction, MPI=myocardial perfusion imaging, PCI=percutaneous coronary intervention.

### KEY QUESTION 1 DIAGNOSTIC ACCURACY OF HEARTFLOW

One new systematic review^1^ agreed with previous findings, reporting good diagnostic accuracy of HeartFlow, and higher specificity for identifying obstructive coronary disease than CCTA alone in patients with suspected coronary disease using a reference standard of FFR during ICA (specificity range = 73% to 76% HeartFlow vs 61% to 64% CCTA alone) (Table 3).^1–3^ The accuracy of HeartFlow was higher than that of CCTA (AUC range = 0.87 to 0.89 HeartFlow vs 0.82 CCTA alone), while sensitivities were similar (84% to 85% HeartFlow vs 86% to 88% CCTA).

Table 3 Diagnostic Accuracy of HeartFlow from Included Systematic Reviews

Systematic Review^a^ | | Celeng, 2018^3^ | Hamon, 2019^2^ | Pontone, 2020^1^
Patient Population | | Patients with stable chest pain with suspected CAD undergoing clinically indicated ICA with FFR after CCTA
Heart-Flow | Sensitivity^b^ [95% CI] | 85% [81, 90] | 84% [80, 88] | 85% [81, 88]
Heart-Flow | Specificity^b^ [95% CI] | 73% [61, 82] | 76%[73, 79] | 75% [72, 78]
Heart-Flow | AUC [95% CI] | 0.87 [NR] | 0.89 [NR] | 0.89 [NR]
CCTA | Sensitivity^b^ [95% CI] | 87% [84, 91] | 86% [85, 88] | 88% [85, 90]
CCTA | Specificity^b^ [95% CI] | 61% [54, 68] | 64% [63, 66] | 64% [61, 66]
CCTA | AUC [95% CI] | NR | 0.82 [NR] | 0.82 [NR]

Notes. Boldface indicates new evidence since 2019 ESP report.

a Each SR included a subset of 9 studies on HeartFlow.

b Per-vessel.

Abbreviations. CAD=coronary artery disease, CCTA=coronary computed tomography angiography, FFR=fractional flow reserve, ICA=invasive coronary angiography.

Seven studies (5 new since 2019 ESP report) published after the most recent systematic reviews generally agreed with the findings of those reviews. Sensitivity (range = 81% to 92%), specificity (range = 68% to 94%), and accuracy (AUC range = 0.82 to 0.94) estimates for HeartFlow varied, but generally showed similar sensitivity and higher specificity and diagnostic accuracy than CCTA alone (Table 4).^4–10^ The variation in estimates among studies may be due to differences in study populations, CCTA procedures (ie, imaging technique), or study methods (eg, whether clinicians interpreting HeartFlow had knowledge of reference standard findings). Multiple studies directly assessing the diagnostic accuracy of HeartFlow compared to FFR during ICA reported similar sensitivities, but higher specificities, than that of CCTA, strengthening our confidence in these findings. However, no studies have assessed diagnostic accuracy in a VA population.

All included studies used a FFR_CT_ cut-off value of ≤ 0.80. An evaluation of the diagnostic performance of HeartFlow according to different FFR_CT_ cut-off values in patients with suspected CAD undergoing invasive FFR found that specificity values were higher with a cut-off of FFR_CT_ ≤ 0.75 compared to FFR_CT_ ≤ 0.80 (75% and 59%, respectively), with acceptable sensitivity (95% for FFR_CT_ = 0.80 and 86% for FFR_CT_ = 0.75).^58^Additionally, a sub-study from an observational Danish study found that in patients with intermediate stenoses on CCTA, an FFR_CT_ score < 0.75 was more predictive of ICA results than a score in the range 0.75 to 0.80.^16^

Table 4 Primary Studies on the Diagnostic Accuracy of HeartFlow^a^

Author, Year (N) | Patient Population | CAD^b^ | Sensitivity^c^ [95% CI] | Specificity^c^ [95% CI] | AUC [95% CI]
Bom, 2021 ^4^; (132) | Suspected CAD and ≥ 30% stenosis on ICA | NR | 90% [83, 96] | 68% [58, 77] | 0.89 [0.83 to 0.93]
Cami, 2020 ^5^; (1,484) | Evaluated for myocardial ischemia | NR | Distal: 92% [NR]; Terminal: 92% [NR] | Distal: 86% [NR]; Terminal: 50% [NR] | Distal: 0.91 [NR]; Terminal: 0.83 [NR]
Driessen, 2019^6^; (157) | Suspected CAD and clinically indicated ICA with FFR | 45% | 90% [84, 95] | 86% [82, 89] | 0.94 [0.92 to 0.96]
Ko, 2019 ^7^; (51) | Suspected CAD and clinically indicated ICA with FFR | 49% | 81% [63, 93] | 85% [73, 93] | 0.90 [0.82 to 0.98]
Pontone, 2019a^8^; (147) | Suspected CAD and clinically indicated ICA with FFR | 45% | 88% [82, 94] | 94% [91, 96] | 0.93 [0.91 to 0.96]
Pontone, 2019b ^9^; (85) | Suspected CAD and clinically indicated ICA with FFR | 57% | 86% [78, 94] | 75% [68, 82] | 0.88 [0.83 to 0.92]
Tanigaki, 2019 ^10^; (152) | Stable CAD identified by CCTA | 46% | 82% [76, 88] | 70% [64, 74] | 0.82 [0.76 to 0.87]

Notes. Boldface indicates new evidence since 2019 ESP report.

a Not included in previous meta-analyses.

b Prevalence of functionally significant CAD classified as at least one vessel with invasive FFR ≤ 0.80.

c Per-vessel.

Abbreviations. CAD=coronary artery disease, CCTA=coronary computed tomography angiography, FFR=fractional flow reserve, ICA=invasive coronary angiography.

### KEY QUESTION 2 DIAGNOSTIC AND THERAPEUTIC IMPACT OF HEARTFLOW

#### Use of Invasive Coronary Angiography

Several clinical scenarios were previously identified for the potential impact of HeartFlow on use of ICA. No new evidence examined the impact of HeartFlow on ICA use in patients directly referred to ICA (scenario 1), or as a substitute for other noninvasive strategies (scenario 2). A single new study examined reduction in ICA with use of HeartFlow in patients referred for CCTA (scenario 3).

##### Scenario 1: Use of HeartFlow in patients who are planned to be directly referred to ICA in lieu of noninvasive evaluation

No new studies examined impact of HeartFlow on the use of ICA in patients planned to be directly referred to ICA. As previously described, the PLATFORM study^11^ compared consecutive cohorts of patients receiving usual care (invasive or noninvasive diagnostic evaluation followed by medical therapy or invasive procedures) or HeartFlow. Findings from this study suggest that use of HeartFlow in patients with new onset chest pain scheduled for elective ICA can reduce the use of coronary angiograms in patients who do not have functionally significant coronary disease. In this trial, use of HeartFlow reduced the 90-day rate of ICA overall from 100% to 40% in patients whose local community physicians planned ICA as the initial test to evaluate chest pain. The rate of nonobstructive ICA was 12% in the HeartFlow group versus 73% in the usual care group (risk difference = −61%, 95% CI [−53, −69]). The rate of obstructive CAD was similar in the 2 groups. Similar findings were reported in a sub-analysis of these patients from German sites.^56^ Our confidence in these findings is limited because the criteria for ordering elective ICA were unclear and may differ across clinical settings, including between VA and non-VA settings. Additionally, these findings are from a single study and it is unknown if further studies would have consistent findings.

##### Scenario 2: Use of HeartFlow as a substitute for other noninvasive testing

No new studies examined impact of HeartFlow on the use of ICA in patients planned for other noninvasive testing. The PLATFORM study showed that HeartFlow did not reduce the use of ICA in patients who were planned for noninvasive testing. Only about 10% of patients who underwent a noninvasive workup needed ICA, whereas 12.5% of HeartFlow patients underwent angiography.^11^ A previously described single-center, pre-post study in Denmark^12^ reported findings that conflicted with the PLATFORM trial, with a reduction in the use of ICA (−4.2 per 100 patients, 95% CI [−6.9, −1.6]) and a reduction in the rate of finding no obstructive disease on ICA (−12.8 per 100 ICAs, 95% CI [−22.2, −3.4]) after switching the preferred noninvasive strategy from myocardial perfusion imaging to CCTA plus selective HeartFlow (in patients with intermediate stenosis on CCTA). However, the risk difference was small and should be considered alongside the negative results of the PLATFORM trial in patients referred for an initially noninvasive evaluation. Our confidence in these findings is limited by inconsistent findings and lack of direct comparison to specific noninvasive strategies, including those routinely used in the VA.

##### Scenario 3: Use of HeartFlow as a part of the clinical pathway for patients who undergo CCTA

One new single-center study^13^ in the US described the impact of implementing HeartFlow in patients without known CAD referred for CCTA. ICA utilization was compared among consecutive patients receiving HeartFlow during a specific time period and a historical control group receiving CCTA alone. This study has major methodological limitations, including use of a historical control group with unclear methods for selection of patients. There were important baseline differences between patients receiving HeartFlow and the historical control group (anginal typicality, prior stress testing, etc), and it is likely that these differences impacted downstream use of ICA. Additionally, introduction of HeartFlow into the clinic may have influenced ICA referral patterns among clinicians. Although ICA use was similar overall (17% [65/387] HeartFlow vs 18% [8/44] historical control), among patients with at least 1 vessel with ≥ 50% diameter stenosis, ICA use was reduced with HeartFlow (45% [55/121] HeartFlow vs 80% [8/10] historical control). Our confidence in these findings is very low, as they are from a single study with severe methodological limitations. In the previously described ADVANCE registry,^54^ overall 90-day ICA use was 43.9%, and several subgroup analyses^22,25,53^ of the registry reported similar findings (the registry did not have a comparison to patients not receiving HeartFlow).

#### Change in Clinical Management

Several new registry- or hospital system-based studies reported changes in clinical management plans or rates of ICA cancellation based on HeartFlow or CCTA alone^14–22^ (Table 5). Most studies compared clinical management plans within a single group of patients, with clinicians making clinical decisions based on CCTA images or HeartFlow FFR_CT_ analyses of the same patients. Rates of changes in clinical management plans among the new studies varied (range = 24% to 55.8%)^17,20,22^ but were generally lower than those previously reported (range = 36% to 66.9%).^18,19,21^ Rates of ICA cancellation ranged from 48% to 91%.^15,16,21^ The variability in these findings likely arises from differences in patient populations (ie, patients with suspected CAD vs those with known CAD or documented stenosis), local variation in clinical management and physician practices, and availability of ICA. One new study^14^ compared management plans between 2 heart teams, randomized to make a treatment decision between percutaneous coronary intervention (PCI) or coronary artery bypass grafting (CABG) based on coronary angiography or on CCTA. Each heart team then had to make a second treatment decision based on results from HeartFlow. Compared to CCTA or ICA, 7% and 6.6% of patients had a treatment decision change between PCI and CABG with the additional HeartFlow information, respectively.

Table 5 Changes in Clinical Management with HeartFlow

Author, Year (N) | Population | Change in Clinical Management
Andreini, 2019 ^14^; (223) | Patients with CAD diagnosed with ICA or CCTA and candidates for PCI or CABG | Change btwn CABG and PCI: 7% (95% CI 3.4, 10.6)^a^ vs CCTA 6.6% (95% CI [3.1, 10.1])^a^ vs ICA
Baggiano, 2020 ^17^; (291) | Symptomatic patients scheduled for ICA + invasive FFR | 28% (95% CI [22.8, 31.2]) ^a^
Curzen, 2016^18^; (200) | Patients with suspected CAD with at least one stenosis (30–90%) on CCTA undergoing nonemergent ICA | 36% (95% CI [29.3, 42.7])^a^
Fairbairn, 2018^19^; (5,083) | Patients with suspected CAD with documented atherosclerosis (>30%) on CCTA | 66.9% (95% CI [64.8, 67.6])
Fares, 2019 ^20^; (207) | Patients with suspected CAD referred for FFRCT | 24% (95% CI [17.4, 30.6]) ^a^
Jang, 2016^21^; (75) | Patients with suspected CAD undergoing CCTA and referred for ICA. | 55%; ICA cancellation: 48%
Jensen, 2018^15^; (774) | Patients with suspected CAD referred to non-emergent ICA or CCTA | ICA cancellation: 75% (high risk), 91% (low-intermediate risk)
Norgaard, 2017 (clinical use)^16^; (1,248) | Patients with suspected CAD undergoing CCTA | ICA cancellation: 66% (95% CI [59, 73])^a^
Shiono, 2019 ^22^; (1,829) | Japanese patients with suspected CAD with documented atherosclerosis (>30%) on CCTA | 55.8% (95% CI [53.5, 58.1]) ^a^

Notes. Boldface indicates new evidence since 2019 ESP report.

a ESP Calculated.

Abbreviations. CABG=coronary artery bypass graft, CAD=coronary artery diseases, CCTA=coronary computed angiography tomography, FFR=fractional flow reserve, ICA=invasive coronary angiography, PCI=percutaneous coronary intervention.

Studies directly evaluated outcomes of clinical relevance in actual practice. However, our confidence in these findings is limited by important methodological weaknesses, including lack of control groups (all patients received HeartFlow in most studies) and unclear blinding of imaging results (ie, the same clinicians made clinical recommendations based on CCTA alone or HeartFlow) in several studies, which may have influenced changes in clinical management plans. Additionally, most studies did not assess whether HeartFlow affected actual clinical management of patients (treatment received) but focused on changes in the initial clinician management plan.

### KEY QUESTION 3 IMPACT OF HEARTFLOW ON CLINICAL OUTCOMES AND COST

Rates of cardiovascular and other adverse events were low and were similar in those receiving HeartFlow or other diagnostic strategies, and in those whose clinical management plans were changed with HeartFlow (including in those who had ICA cancelled based on HeartFlow results) and those whose clinical management plans were not changed (Table 6).^11,15,16,19,21,24,26,54^ One new sub-analysis of the NXT trial (designed to examine the diagnostic accuracy of HeartFlow)^59^ reported a longer-term rate of major adverse cardiac events (MACE; 9.7% at a median of 4.7 years) among patients receiving HeartFlow, but did not compare MACE rates to those in patients utilizing other diagnostic strategies.^26^ Although MACE and other clinical event rates were consistently low, only the PLATFORM trial compared event rates in patients receiving HeartFlow to other diagnostic strategies, and only a single study included follow-up longer than 1 year.

Table 6 Cardiac and Clinical Events

Author, Year | Follow-up | MACE or Other Adverse Cardiac Events
Douglas, 2015^11^/2016^24^ | 90 days; 1 year | 90 days: 2 (0.7%) HeartFlow vs 0 usual care MACE; 1 year: 2 (0.7%) HeartFlow vs 2 (1.0%) usual care MACE (0 in patients whose ICA was canceled based on HeartFlow results)
Fairbairn, 2018^19^; Nous, 2021 ^54^ | 90 days; 1 year | 90 days: 19 (0.4%) MACE; 1 year: 59 (1.2%) MACE
Ihdayhid, 2019 ^26^ | 4.7 years (median) | 20 MACE (9.7%)
Jang, 2016^21^ | 1 year | No significant difference in cardiovascular events between patients with changed vs unchanged management with HeartFlow (data NR)
Jensen, 2018^15^ | 90 days | 14 (1.8%) clinical adverse events (0 in patients whose ICA was canceled based on HeartFlow results)
Norgaard, 2017^16^ (clinical) | 90 days | 0 serious adverse cardiac events (including in patients whose ICA was canceled based on HeartFlow results)

Notes. Boldface indicates new evidence since 2019 ESP report.

Abbreviations. ICA=invasive coronary angiography, MACE=major adverse cardiovascular event.

No new studies examined cost or quality of life outcomes. As previously described, quality of life scores in the PLATFORM trial^24,57^ were generally similar between groups, with a greater improvement in quality of life reported with HeartFlow in the planned noninvasive subgroup. Mean costs at 90 days and 1 year were lower in the HeartFlow cohort compared to the usual care cohort in the subgroup of patients planned to receive ICA, but no differences in costs were observed between the groups in patients planned to receive noninvasive testing.^24,57^

### CONSIDERATIONS FOR THE USE OF HEARTFLOW IN VA

The potential impact of HeartFlow depends on the use of CCTA because CCTA images are needed for the HeartFlow FFR_CT_ analysis. The VA currently employs the 2012 American College of Cardiology Foundation and American Heart Association guidance for diagnosis of CAD, which recommends CCTA only for those who are unable to exercise or who have contraindications to stress testing.^60,61^ Data from the VA national CDW shows that around 2,000 VA patients without a diagnosis of CAD or prior history of revascularization or ICA underwent CCTA testing each year from 2018 to 2020 (1,925 patients in 2018, 2,007 patients in 2019 and 1,828 patients in 2020). Among facilities performing at least 1 CCTA, more than 80% of VA sites reported fewer than 50 CCTAs during the calendar years 2018 to 2020 (Figure 2), with around 40% to 60% of VA sites performing 10 CCTAs or fewer. Only 3 to 4 VA sites reported doing 100 CCTAs or more per year from 2018 to 2020.

Figure 2 Usage of Coronary Computed Tomography Angiography (CCTA) Among VA Stations Performing at Least 1 CCTA Each Calendar Year

Among VA patients undergoing CCTA, only 18.5% underwent ICA within 90 days after CCTA, indicating that most patients receiving CCTA have normal or non-obstructive results and do not end up requiring ICA or have extensive coronary artery disease not amenable to ICA intervention. In these cases, further imaging, including HeartFlow FFR_CT_ analysis, is usually not necessary. Similar rates of ICA after CCTA in patients with suspected but unknown CAD have been reported in other studies (9.6% to 16%).^62–65^

CCTA is generally used less often in the US compared to Europe due to differences in guidance recommendations, reimbursement structures, and clinical practices and training.^66^ Guidance from the European Society of Cardiology^67^ and the National Institute for Health and Care Excellence^68^ in the UK recommend use of CCTA as a first-line diagnostic strategy for patients with stable chest pain or chronic coronary syndrome. In an analysis of CCTA use among the Medicare population from 2006 to 2016, CCTA use in the US peaked in 2007 (210.3 per 100,000), and then declined until 2014, after which CCTA usage began to rise again, reaching 131.0 per 100,000 in 2016.^69^ A recent American College of Cardiology State-of-the-Art Review outlined supportive evidence for expanded use of CCTA in the US.^66^ However, barriers to increasing the use of CCTA in the US remain, including limited access to equipment, limited availability and support of technical training for clinicians, and lack of updated guidance for use of CCTA.

The potential impact of targeted HeartFlow use in patients referred for CCTA in the VA was estimated in the previous ESP report from data on the sensitivity and specificity of HeartFlow and CCTA alone. Using assumptions for the prevalence of patients with intermediate-stenosis lesions on CCTA, the proportion of these patients who have functionally significant CAD, and the proportion of patients with positive CCTA that undergo ICA, an estimated 34 ICAs could be prevented for every 1,000 patients undergoing CCTA.^29^

### ADEQUACY OF CCTA IMAGES FOR HEARTFLOW FFR_CT_

HeartFlow FFR_CT_ analysis requires adequate-quality CCTA images to estimate FFR data. In studies on the therapeutic and clinical impact of HeartFlow reporting rates of acceptance of CCTA images, 79% to 98.6% of images were adequate for HeartFlow FFR_CT_ analysis. Variation in equipment quality and physician and CT technologist expertise may influence the adequacy of CCTA images and are important considerations for potential implementation of HeartFlow. When CCTA images are rejected due to poor image quality, CCTA must be repeated to use HeartFlow.

## SUMMARY AND DISCUSSION

New evidence did not resolve the evidence gaps identified in the 2019 ESP report. New evidence on the diagnostic accuracy of HeartFlow agreed with findings from the 2019 ESP report, confirming that HeartFlow has good diagnostic accuracy and is more specific than CCTA alone when compared with the reference standard of invasive FFR. No new studies assessed reduction in ICA use with HeartFlow use in patients directly referred to ICA or as a substitute for other noninvasive tests. In the PLATFORM trial,^11^ use of HeartFlow reduced the use of coronary angiography in patients directly referred to ICA. However, use of HeartFlow as a substitute for other noninvasive tests led to a higher rate of ICA use in this trial.^11^ New evidence showed no difference in ICA use overall with the use of HeartFlow in patients referred for CCTA, but a reduction in ICA use among patients with at least 1 vessel with ≥ 50% diameter stenosis.^13^ However, severe methodological limitations of this study limit our confidence in these findings. HeartFlow likely changes treatment plans compared to decisions made based on CCTA alone, but the impact on actual treatment received is less clear. Although the specificity of HeartFlow is improved over CCTA alone, the impact on downstream utilization of ICA needs to be verified.

New evidence supported previous findings of low short-term (90 days to 1 year) rates of cardiac events with similar rates in those receiving HeartFlow and other diagnostic strategies, and in those whose clinical management plans changed because of HeartFlow and those whose management plans were unchanged. New evidence on longer-term clinical outcomes showed that MACE rates at around 5 years increased to almost 10% (compared to <2% at 90 days to 1 year) among those receiving HeartFlow. However, comparison of clinical outcomes in patients receiving HeartFlow to other diagnostic strategies are lacking. The findings of generally low clinical event rates align with those reported in the PROMISE trial, which examined outcomes of stable symptomatic outpatients without known CAD randomly assigned to receive CCTA or functional testing (all-cause death/myocardial infarction/unstable angina: 3.1% CCTA vs 3.0% functional testing, median follow-up of 26.1 months).^70^ These findings question the overall impact of diagnostic testing strategy on clinical outcomes, including the potential of HeartFlow to impact downstream clinical outcomes. Given the apparently limited impact of diagnostic testing strategy on clinical outcomes, studies of HeartFlow have emphasized the potential for a reduction in the unnecessary use of invasive procedures. However, clinical practice patterns, including routine use of ICA, may vary across different clinical settings. It is important to consider whether reduction in ICA use is appropriate as the key outcome for determining the impact of HeartFlow in all settings, specifically in settings where ICA is not routinely used.

Key considerations for the use of HeartFlow in the VA are the availability and frequency of use of CCTA, technical training for clinicians, and potential challenges of integrating HeartFlow into the clinical workflow. The relatively low number of CCTAs performed in the VA, along with the low rate of ICA after CCTA, suggest that regular use of HeartFlow among all patients referred CCTA may have a low impact on ICA use in the VA. However, if utilization of CCTA within the VA increases in light of updated guidance from the European Society of Cardiology^67^ and a review of the evidence by the American College of Cardiology^69^ supporting use of CCTA as a first-line diagnostic strategy, HeartFlow has the potential to reduce ICA use in certain clinical scenarios, including as a targeted add-on for patients with CCTA findings that are borderline for obstructive disease. Although few VA sites performed more than 100 CCTAs per year, assessment of the impact of HeartFlow in these high-volume centers could identify the potential clinical implications of use of HeartFlow within the VA. Another important consideration is the low volume of CCTAs within the VA may impact image quality for HeartFlow analysis. VA sites with less technical expertise in conducting CCTAs may experience a higher rate of rejection of images for HeartFlow FFR_CT_ analysis, and it may be necessary for sites to perform a minimum number of CCTAs per year to stay adequately trained and experienced in CCTA techniques.

Other FFR_CT_ algorithms, including Siemens Healthcare cFFR, Canon Medical Systems CT-FFR and independent, locally developed machine learning and reduced order modeling techniques are alternatives to HeartFlow.^2,3,38^ Although none of these technologies are yet commercially available or FDA cleared, they can be used within individual clinics, hospitals, or research environments without the need for analyses by an outside entity. The VA may consider developing its own approach to noninvasive FFR modeling, but evidence on the diagnostic and clinical impact of these alternatives is minimal and was outside the scope of this review.

### LIMITATIONS

There are several important limitations of the evidence base. No randomized controlled trials investigated the impact of HeartFlow on diagnostic or clinical outcomes. Cohort studies comparing HeartFlow to other noninvasive strategies (including CCTA alone) or ICA were often limited by unbalanced baseline patient characteristics (eg, type of chest pain, cardiac risk factors, demographics, etc). These differences may influence outcomes (ie, one group may be more likely to be referred to ICA due to type of chest pain or cardiac risk factors). Statistical adjustment for baseline differences between groups was inadequate, or unable to be fully assessed due to lack of information on adjustment methods. Without balanced comparison groups, differences in outcomes could have been due to patient characteristics linked to ICA referrals rather than use of HeartFlow. To determine the impact of HeartFlow compared to other diagnostic strategies, an ideal trial would enroll patients at a distinct point in their diagnostic workup (ie, at symptom onset) and randomize them to receive either HeartFlow or another invasive or noninvasive strategy for diagnosis of CAD, equalizing patient characteristics across groups. Adequate sample size, blinding of patients and outcome assessors, and standardized assessment of outcomes over a specific period of time are also important.

Limitations of our review methods include use of a second reviewer check during study selection and data abstraction rather than dual independent review. Additionally, only FDA-cleared FFR_CT_ technologies were eligible for this review, limiting our assessment to studies of HeartFlow FFR_CT_ analysis. No studies examined HeartFlow compared to other noninvasive FFR_CT_ technologies (locally developed algorithms, etc) and the clinical impact of these alternatives compared to HeartFlow is unknown.

### EVIDENCE GAPS AND FUTURE RESEARCH

Substantial gaps in the evidence remain. Most importantly, no studies have assessed HeartFlow in a VA setting. The utility of HeartFlow depends on the characteristics of patients who undergo diagnostic testing and on how clinical decisions are made within a particular setting. Patient characteristics and clinical pathways may differ between non-VA and VA populations and settings, and the impact of HeartFlow within the VA remains unknown. Only 2 studies examined the impact of HeartFlow on the use of ICA in patients referred for noninvasive testing, and comparison of HeartFlow to specific noninvasive strategies is lacking. Clinical decisions and diagnostic pathways likely differ within the VA compared to those in community settings in studies of HeartFlow and direct evidence about how HeartFlow compares to diagnostic tests widely used in the VA is needed. Additionally, only a single study (with serious methodological limitations) examined the impact on ICA use of adding HeartFlow to the clinical pathway for patients referred for CCTA, which is the clinical scenario promoted on the manufacturer website.^40^ Controlled studies of ICA rates in patients with suspected coronary disease receiving CCTA or other noninvasive strategies and comparing HeartFlow to specific noninvasive strategies are needed.

### CONCLUSIONS

New evidence did not sufficiently address the evidence gaps identified in the 2019 ESP report. The impact of regularly utilizing HeartFlow for all patients referred for CCTA within the VA is likely low, given the relatively low number of CCTAs performed in the VA and the unclear impact of HeartFlow compared to noninvasive strategies currently used within the VA. However, use of HeartFlow in facilities with a high volume of CCTAs in specific clinical scenarios may have the potential to reduce unnecessary use of coronary angiography. Short-term rates of adverse cardiac events are likely low and do not differ in those receiving HeartFlow or other diagnostic strategies, but additional research is needed on longer-term clinical outcomes comparing rates of adverse cardiac events between HeartFlow and other diagnostic strategies. Research in VA settings and comparing HeartFlow to specific noninvasive strategies is needed to determine the potential impact of HeartFlow within the VA.

## ACKNOWLEDGMENTS

This topic was developed in response to a request from the VA Health Services Research and Development Service for an updated evidence review on the diagnostic, therapeutic, and clinical impact of FFR_CT_ technologies in the noninvasive diagnosis of CAD. The scope was further developed with input from Operational Partners (below) and the ESP Coordinating Center review team.

The authors gratefully acknowledge Kathryn Vela for literature searching and Rachel Ward for editorial and citation management support, and the following individuals for their contributions to this project:

### Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on the draft report; and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- David Atkins, MD, MPH
  VA HSR&D Director

### Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Paul Hess, MD
  University of Colorado School of Medicine
- Jeffrey Chenoweth, MD
  Acting Director, VHA National Radiology Program

### Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.

## REFERENCES

1 Pontone G, Guaricci AI, Palmer SC, . Diagnostic performance of non-invasive imaging for stable coronary artery disease: A meta-analysis. Int J Cardiol. 2020;300:276–281.31748186
2 Hamon M, Geindreau D, Guittet L, Bauters C, Hamon M. Additional diagnostic value of new ct imaging techniques for the functional assessment of coronary artery disease: A meta-analysis. European Radiology. 2019;29(6):3044–3061.30617482
3 Celeng C, Leiner T, Maurovich-Horvat P, . Anatomical and functional computed tomography for diagnosing hemodynamically significant coronary artery disease: A meta-analysis. JACC: Cardiovascular Imaging. 2018:S1936–1878X(1918)30681–30688.
4 Bom MJ, Driessen RS, Kurata A, . Diagnostic value of comprehensive on-site and off-site coronary ct angiography for identifying hemodynamically obstructive coronary artery disease. Journal of Cardiovascular Computed Tomography. 2021;15(1):37–45.32540206
5 Cami E, Tagami T, Raff G, . Importance of measurement site on assessment of lesion-specific ischemia and diagnostic performance by coronary computed tomography angiography-derived fractional flow reserve. Journal of Cardiovascular Computed Tomography. 2020;29:29.
6 Driessen RS, Danad I, Stuijfzand WJ, . Comparison of coronary computed tomography angiography, fractional flow reserve, and perfusion imaging for ischemia diagnosis. Journal of the American College of Cardiology. 2019;73(2):161–173.30654888
7 Ko BS, Linde JJ, Ihdayhid AR, . Non-invasive ct-derived fractional flow reserve and static rest and stress ct myocardial perfusion imaging for detection of haemodynamically significant coronary stenosis. The International Journal of Cardiovascular Imaging. 2019;35(11):2103–2112.31273632
8 Pontone G, Baggiano A, Andreini D, . Stress computed tomography perfusion versus fractional flow reserve ct derived in suspected coronary artery disease: The PERFECTION study. JACC: Cardiovascular Imaging. 2019;12(8 Pt 1):1487–1497.30343073
9 Pontone G, Baggiano A, Andreini D, . Dynamic stress computed tomography perfusion with a whole-heart coverage scanner in addition to coronary computed tomography angiography and fractional flow reserve computed tomography derived. JACC: Cardiovascular Imaging. 2019;12(12):2460–2471.31005531
10 Tanigaki T, Emori H, Kawase Y, . Qfr versus FFR derived from computed tomography for functional assessment of coronary artery stenosis. JACC: Cardiovascular Interventions. 2019;12(20):2050–2059.31648766
11 Douglas PS, Pontone G, Hlatky MA, . Clinical outcomes of fractional flow reserve by computed tomographic angiography-guided diagnostic strategies vs. Usual care in patients with suspected coronary artery disease: The prospective longitudinal trial of FFR(ct): Outcome and resource impacts study. European Heart Journal. 2015;36(47):3359–3367.26330417
12 Norgaard BL, Gormsen LC, Botker HE, . Myocardial perfusion imaging versus computed tomography angiography-derived fractional flow reserve testing in stable patients with intermediate-range coronary lesions: Influence on downstream diagnostic workflows and invasive angiography findings. Journal of the American Heart Association. 2017;6(8):22.
13 Rabbat M, Leipsic J, Bax J, . Fractional flow reserve derived from coronary computed tomography angiography safely defers invasive coronary angiography in patients with stable coronary artery disease. Journal of Clinical Medicine. 2020;9(2):24.
14 Andreini D, Modolo R, Katagiri Y, . Impact of fractional flow reserve derived from coronary computed tomography angiography on heart team treatment decision-making in patients with multivessel coronary artery disease: Insights from the syntax iii revolution trial. Circulation: Cardiovascular Interventions. 2019;12(12):e007607.31833413
15 Jensen JM, Bøtker HE, Mathiassen ON, . Computed tomography derived fractional flow reserve testing in stable patients with typical angina pectoris: Influence on downstream rate of invasive coronary angiography. European Heart Journal Cardiovascular Imaging. 2018;19(4):405–414.28444153
16 Norgaard BL, Hjort J, Gaur S, . Clinical use of coronary cta-derived FFR for decision-making in stable cad. JACC: Cardiovascular Imaging. 2017;10(5):541–550.27085447
17 Baggiano A, Fusini L, Del Torto A, . Sequential strategy including FFR<sub>ct</sub> plus stress-ctp impacts on management of patients with stable chest pain: The stress-ctp ripcord study. Journal of Clinical Medicine. 2020;9(7):08.
18 Curzen NP, Nolan J, Zaman AG, Norgaard BL, Rajani R. Does the routine availability of ct-derived FFR influence management of patients with stable chest pain compared to ct angiography alone?: The FFRCT ripcord study. JACC Cardiovascular Imaging. 2016;9(10):1188–1194.27568119
19 Fairbairn TA, Nieman K, Akasaka T, . Real-world clinical utility and impact on clinical decision-making of coronary computed tomography angiography-derived fractional flow reserve: Lessons from the advance registry. European Heart Journal. 2018;39(41):3701–3711.30165613
20 Fares A, Alaiti MA, Alkhalil A, . Real world utilization of computed tomography derived fractional flow reserve: Single center experience in the united states. Cardiovascular Revascularization Medicine. 2019;20(12):1043–1047.30833210
21 Jang J, Krishnaswami A, Rogers C, Hung Y, Sengupta S. The impact of fractional flow reserve derived from coronary computed tomography angiography in a managed healthcare system – kaiser permanente northern california [abstract #50]. Journal of Cardiovascular Computed Tomography. 2016;10(3):S1–S96.
22 Shiono Y, Matsuo H, Kawasaki T, . Clinical impact of coronary computed tomography angiography-derived fractional flow reserve on japanese population in the advance registry. Circulation Journal. 2019;83(6):1293–1301.30996150
23 Van Belle E, Raposo L, Bravo Baptista S, . Impact of an interactive ct/FFR<sub>ct</sub> interventional planner on coronary artery disease management decision making. JACC: Cardiovascular Imaging. 2021;04:04.
24 Douglas PS, De Bruyne B, Pontone G, . 1-year outcomes of FFRCT-guided care in patients with suspected coronary disease: The platform study. Journal of the American College of Cardiology. 2016;68(5):435–445.27470449
25 Anastasius M, Maggiore P, Huang A, . The clinical utility of FFRCT stratified by age. Journal of Cardiovascular Computed Tomography. 2020;23:23.
26 Ihdayhid AR, Norgaard BL, Gaur S, . Prognostic value and risk continuum of noninvasive fractional flow reserve derived from coronary ct angiography. Radiology. 2019;292(2):343–351.31184558
27 Patel MR, Norgaard BL, Fairbairn TA, . 1-year impact on medical practice and clinical outcomes of FFR<sub>ct</sub>: The advance registry. JACC: Cardiovascular Imaging. 2020;13(1 Pt 1):97–105.31005540
28 Norgaard BL, Mortensen MB, Parner E, . Clinical outcomes following real-world computed tomography angiography-derived fractional flow reserve testing in chronic coronary syndrome patients with calcification. European Heart Journal Cardiovascular Imaging. 2020;13:13.
29 Helfand M, Anderson J, Peterson K, D B. Evidence assist: Coronary computed tomography angiography innovations in noninvasive diagnosis of coronary artery disease. Washington, DC: Evidence Synthesis Program, Health Services Research and Development Service, Office of Research and Development, Department of Veterans Affairs. VA ESP Project #09-199; 2019. Available at: https://www.hsrd.research.va.gov/publications/esp/reports.cfm;2019.
30 Katz D, Gavin M. In the clinic: Stable ischemic heart disease. Annals of Internal Medicine. 2019.
31 Lan W-C, Chen Y-H, Liu S-H. Non-invasive imaging modalities for the diagnosis of coronary artery disease: The present and the future. Tzu Chi Medical Journal. 2013;25(4):206–212.
32 Siontis GC, Mavridis D, Greenwood JP, . Outcomes of non-invasive diagnostic modalities for the detection of coronary artery disease: Network meta-analysis of diagnostic randomised controlled trials. BMJ. 2018;360:k504.29467161
33 Haase R SP, Gueret P, . . Diagnosis of obstructive coronary artery disease using computed tomography angiography in patients with stable chest pain depending on clinical probability and in clinically important subgroups: Meta-analysis of individual patient data. BMJ (Clinical Research Ed). 2019;365(l1945).
34 Hecht HS, Narula J, Fearon WF. Fractional flow reserve and coronary computed tomographic angiography: A review and critical analysis. Circulation Research. 2016;119(2):300–316.27390333
35 Leber WA. Is FFR-ct a “game changer” in the diagnostic management of stable coronary artery disease? Herz. 2016;41(5):398–404.27393032
36 Xie X, Zheng M, Wen D, Li Y, Xie S. A new cfd based non-invasive method for functional diagnosis of coronary stenosis. Biomedical Engineering Online. 2018;17(1):36.29566702
37 Ball C, Pontone G, Rabbat M. Fractional flow reserve derived from coronary computed tomography angiography datasets: The next frontier in noninvasive assessment of coronary artery disease. Biomedical Research International. 2018;2018:2680430.
38 Khav N IA, Ko B Ct-derived fractional flow reserve (ct-FFR) in the evaluation of coronary artery disease. Heart, Lung & Circulation. 2020;29:1621–1632.
39 HeartFlow. HeartFlow. 2018; https://www.heartflow.com/. Accessed April 30, 2019.
40 HeartFlow Inc. Non-invasive cardiac test. https://www.heartflow.com/patients/overview/. Accessed April, 2021.
41 ECRI Institute. Ffrct software (HeartFlow, inc.) for evaluating coronary artery diease. 2020.
42 Huang A MP, Brown RA, . . Ct-derived fractional flow reserve (ffrct): From gatekeeping to roadmapping. Canadian Association of Radiologists Journal. 2020;71(2):201–207.32063007
43 Chen J WL, Pope KL, Meek LJ, Rosamond T, Walker CM. Ffrct: Current status. AJR Am J Roentgenol. 2020;216(3):640–648.33377794
44 NICE. Qangio xa 3d/qfr imaging software for assessing coronary obstructions - medtech innovation briefing (mib146). 2018.
45 Ernst CB. HeartFlow announces decision by centers for medicare & medicaid services to assign a new technology payment classification to HeartFlow® ffrct analysis. 2017; https://www.businesswire.com/news/home/20171106005472/en/HeartFlow-Announces-Decision-Centers-Medicare-Medicaid-Services. Accessed March 19, 2019.
46 New policy decisions give millions access to HeartFlow ffrct analysis. 2018; https://www.dicardiology.com/content/new-policy-decisions-give-millions-access-heartflow-ffrct-analysis. Accessed March 19, 2019.
47 Whiting P, Savović J, Higgins JP, . Robis: A new tool to assess risk of bias in systematic reviews was developed. Journal of Clinical Epidemiology. 2016;69:225–234.26092286
48 Whiting P, Rutjes AW, Westwood ME, . Quadas-2: A revised tool for the quality assessment of diagnostic accuracy studies. Annals of Internal Medicine. 2011;155:529–536.22007046
49 Sterne JA, Hernán MA, Reeves BC, . Robins-i: A tool for assessing risk of bias in non-randomised studies of interventions. BMJ. 2016;355:i4919.27733354
50 Murad MH SS, Haffar S, Bazerbachi F. Methodological quality and synthesis of case series and case reports. BMJ Evidence-Based Medicine. 2018;23(2):60–63.
51 Berkman ND, Lohr KN, Ansari M, . Grading the strength of a body of evidence when assessing health care interventions for the effective health care program of the agency for healthcare research and quality: An update methods guide for effectiveness and comparative effectiveness reviews. Rockville, MD: Agency for Healthcare Research and Quality;2013.
52 US Department of Veterans Affairs. VA informatics and computing infrastructure (vinci). https://www.hsrd.research.va.gov/for_researchers/vinci/. Accessed April 23, 2019.
53 Fairbairn TA, Dobson R, Hurwitz-Koweek L, . Sex differences in coronary computed tomography angiography-derived fractional flow reserve: Lessons from advance. JACC: Cardiovascular Imaging. 2020;13(12):2576–2587.32861656
54 Nous F, Budde RPJ, Fairbairn TA, . Temporal changes in FFR<sub>ct</sub>-guided management of coronary artery disease - lessons from the advance registry. Journal of Cardiovascular Computed Tomography. 2021;15(1):48–55.32418861
55 Pontone G, Weir-McCall JR, Baggiano A, . Determinants of rejection rate for coronary ct angiography fractional flow reserve analysis. Radiology. 2019;292(3):597–605.31335283
56 Colleran R, Douglas PS, Hadamitzky M, . An FFRCT diagnostic strategy versus usual care in patients with suspected coronary artery disease planned for invasive coronary angiography at german sites: One-year results of a subgroup analysis of the platform (prospective longitudinal trial of FFRCT: Outcome and resource impacts) study. Open Heart. 2017;4(1).
57 Hlatky MA, De Bruyne B, Pontone G, . Quality-of-life and economic outcomes of assessing fractional flow reserve with computed tomography angiography: Platform. Journal of the American College of Cardiology. 2015;66(21):2315–2323.26475205
58 Matsumura-Nakano Y, Kawaji T, Shiomi H, . Optimal cutoff value of fractional flow reserve derived from coronary computed tomography angiography for predicting hemodynamically significant coronary artery disease. Circulation Cardiovascular imaging. 2019;12(8):e008905.31525085
59 Norgaard BL, Leipsic J, Gaur S, . Diagnostic performance of noninvasive fractional flow reserve derived from coronary computed tomography angiography in suspected coronary artery disease: The nxt trial (analysis of coronary blood flow using ct angiography: Next steps). Journal of the American College of Cardiology. 2014;63(12):1145–1155.24486266
60 Fihn SD, Blankenship JC, Alexander KP, . 2014 acc/aha/aats/pcna/scai/sts focused update of the guideline for the diagnosis and management of patients with stable ischemic heart disease. Circulation. 2014;130(19):1749–1767.25070666
61 Fihn SD, Gardin JM, Abrams J, . 2012 accf/aha/acp/aats/pcna/scai/sts guideline for the diagnosis and management of patients with stable ischemic heart disease: Executive summary: A report of the american college of cardiology foundation/american heart association task force on practice guidelines, and the american college of physicians, american association for thoracic surgery, preventive cardiovascular nurses association, society for cardiovascular angiography and interventions, and society of thoracic surgeons. Circulation. 2012;126(25):3097–3137.23166210
62 Jorgensen ME, Andersson C, Norgaard BL, . Functional testing or coronary computed tomography angiography in patients with stable coronary artery diease. Journal of the American College of Cardiology. 2017;69(14):1761–1770.28385304
63 Hachamovitch R, Nutter B, Hlatky MA, . Patient management after noninvasive cardiac imaging results from sparc (study of myocardial perfusion and coronary anatomy imaging roles in coronary artery disease). Journal of the American College of Cardiology. 2012;59(5):462–474.22281249
64 Zorlak A, Zorlak A, Thomassen A, . Patients with suspected coronary artery disease referred for examinations in the era of coronary computed tomography angiography. American Journal of Cardiology. 2015;116(3):344–349.
65 Bittencourt MS, Hulten EA, Murthy VL, . Clinical outcomes after evaluation of stable chest pain by coronary computed tomographic angiography versus usual care: A meta-analysis. Circulation: Cardiovascular Imaging. 2016;9(4).
66 Abdelrahman KM, Chen MY, Dey AK, . Coronary computed tomography angiography from clinical uses to emerging technologies. Journal of the American College of Cardiology. 2020;76(10):1126–1243.
67 Knuuti J, Wijns W, Saraste A, . 2019 esc guidelines for the diagnosis and management of chronic coronary syndromes. European Heart Journal. 2020;41:407–477.31504439
68 NICE. HeartFlow FFRCT for estimating fractional flow reserve from coronary ct angiography. 2017.
69 Levin DC, Parker L, Halpern EJ, Rao VM. Coronary ct angiography: Reversal of earlier utilization trends. American College of Radiology. 2018;16:147–155.
70 Hoffmann U, Ferencik M, Udelson JE, . Prognostic value of noninvasive cardiovascular testing in patients with stable chest pain: Insights from the promise trial (prospective multicenter imaging study for evaluation of chest pain). Circulation. 2017;135(24):2320–2332.28389572

## Supplemental Materials

### APPENDIX A SEARCH STRATEGIES

1. Search for current systematic reviews (limited to last 7 years); Date Searched: 2-23-21
A. Bibliographic databases | # | Search Statement | Results
MEDLINE: Systematic Reviews; [Ovid MEDLINE(R) ALL 1946 to February 22, 2021] | [underlined: 1] | [underlined: (FFFRct or CT-FFR* or ctFFR* or FFRct* or CT-based FFR* or FFR CT or noninvasive FFR or noninvasive fractional flow reserve or non-invasive FFR or non-invasive fractional flow reserve).mp.] | [underlined: 376]
MEDLINE: Systematic Reviews; [Ovid MEDLINE(R) ALL 1946 to February 22, 2021] | [underlined: 2] | exp Fractional Flow Reserve, Myocardial/ or (Fractional Flow Reserve or FFR).mp. | [underlined: 4878]
MEDLINE: Systematic Reviews; [Ovid MEDLINE(R) ALL 1946 to February 22, 2021] | [underlined: 3] | [underlined: exp Computed Tomography Angiography/] | [underlined: 11297]
MEDLINE: Systematic Reviews; [Ovid MEDLINE(R) ALL 1946 to February 22, 2021] | [underlined: 4] | [underlined: (Computed Tomography Angiogra* or CCTA or coronary CT angiogra* or CT coronary angiogra*).mp.] | [underlined: 21196]
MEDLINE: Systematic Reviews; [Ovid MEDLINE(R) ALL 1946 to February 22, 2021] | [underlined: 5] | [underlined: 3 or 4] | [underlined: 21196]
MEDLINE: Systematic Reviews; [Ovid MEDLINE(R) ALL 1946 to February 22, 2021] | [underlined: 6] | [underlined: 2 and 5] | [underlined: 663]
MEDLINE: Systematic Reviews; [Ovid MEDLINE(R) ALL 1946 to February 22, 2021] | [underlined: 7] | [underlined: 1 or 6] | [underlined: 733]
MEDLINE: Systematic Reviews; [Ovid MEDLINE(R) ALL 1946 to February 22, 2021] | [underlined: 8] | [underlined: (systematic review.ti. or meta-analysis.pt. or meta-analysis.ti. or systematic literature review.ti. or this systematic review.tw. or pooling project.tw. or (systematic review.ti,ab. and review.pt.) or meta synthesis.ti. or meta-analy*.ti. or integrative review.tw. or integrative research review.tw. or rapid review.tw. or umbrella review.tw. or consensus development conference.pt. or practice guideline.pt. or drug class reviews.ti. or cochrane database syst rev.jn. or acp journal club.jn. or health technol assess.jn. or evid rep technol assess summ.jn. or jbi database system rev implement rep.jn. or (clinical guideline and management).tw. or ((evidence based.ti. or evidence-based medicine/ or best practice*.ti. or evidence synthesis.ti,ab.) and (((review.pt. or diseases category/ or behavior.mp.) and behavior mechanisms/) or therapeutics/ or evaluation studies.pt. or validation studies.pt. or guideline.pt. or pmcbook.mp.)) or (((systematic or systematically).tw. or critical.ti,ab. or study selection.tw. or ((predetermined or inclusion) and criteri*).tw. or exclusion criteri*.tw. or main outcome measures.tw. or standard of care.tw. or standards of care.tw.) and ((survey or surveys).ti,ab. or overview*.tw. or review.ti,ab. or reviews.ti,ab. or search*.tw. or handsearch.tw. or analysis.ti. or critique.ti,ab. or appraisal.tw. or (reduction.tw. and (risk/ or risk.tw.) and (death or recurrence).mp.)) and ((literature or articles or publications or publication or bibliography or bibliographies or published).ti,ab. or pooled data.tw. or unpublished.tw. or citation.tw. or citations.tw. or database.ti,ab. or internet.ti,ab. or textbooks.ti,ab. or references.tw. or scales.tw. or papers.tw. or datasets.tw. or trials.ti,ab. or meta-analy*.tw. or (clinical and studies).ti,ab. or treatment outcome/ or treatment outcome.tw. or pmcbook.mp.))) not (letter or newspaper article).pt.] | [underlined: 438670]
MEDLINE: Systematic Reviews; [Ovid MEDLINE(R) ALL 1946 to February 22, 2021] | [underlined: 9] | [underlined: 7 and 8] | [underlined: 31]
MEDLINE: Systematic Reviews; [Ovid MEDLINE(R) ALL 1946 to February 22, 2021] | [underlined: 10] | [underlined: Limit 9 to English language only] | [underlined: 31]
MEDLINE: Systematic Reviews; [Ovid MEDLINE(R) ALL 1946 to February 22, 2021] | [underlined: 11] | [underlined: Limit 10 to yr=”2019-Current”] | [underlined: 9]
CDSR: Protocols and Reviews; [EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 19, 2021] | [underlined: 1] | [underlined: (FFFRct or CT-FFR* or ctFFR* or FFRct* or CT-based FFR* or FFR CT or noninvasive FFR or noninvasive fractional flow reserve or non-invasive FFR or non-invasive fractional flow reserve).mp.] | [underlined: 0]
CDSR: Protocols and Reviews; [EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 19, 2021] | [underlined: 2] | [underlined: (Fractional Flow Reserve, Myocardial).kw. or (Fractional Flow Reserve or FFR).mp.] | [underlined: 4]
CDSR: Protocols and Reviews; [EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 19, 2021] | [underlined: 3] | [underlined: (Computed Tomography Angiography).kw.] | [underlined: 0]
CDSR: Protocols and Reviews; [EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 19, 2021] | [underlined: 4] | [underlined: (Computed Tomography Angiogra* or CCTA or coronary CT angiogra* or CT coronary angiogra*).mp.] | [underlined: 25]
CDSR: Protocols and Reviews; [EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 19, 2021] | [underlined: 5] | [underlined: 3 or 4] | [underlined: 25]
CDSR: Protocols and Reviews; [EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 19, 2021] | [underlined: 6] | [underlined: 2 and 5] | [underlined: 0]
CDSR: Protocols and Reviews; [EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 19, 2021] | [underlined: 7] | [underlined: 1 or 6] | [underlined: 0]
CDSR: Protocols and Reviews; [EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 19, 2021] | [underlined: 8] | [underlined: limit 7 to yr=”2019-Current”] | [underlined: 0]
B. Non-bibliographic databases | [underlined: Evidence:] | | [underlined: Results]
AHRQ: evidence reports, technology assessments, U.S Preventative Services Task Force Evidence Synthesis | http://www.ahrq.gov/research/findings/evidence-based-reports/search.html; Search: FFFRct; fractional flow reserve; non-invasive CAD imaging; Coronary Computed Tomography Angiography; coronary CT angiography; CCTA | | [underlined: 0]
CADTH | https://www.cadth.ca; Search: FFFRct; fractional flow reserve; non-invasive CAD imaging; Coronary Computed Tomography Angiography; coronary CT angiography; CCTA | | [underlined: 0]
ECRI Institute | https://www.ecri.org/Pages/default.aspx; Search: FFFRct; fractional flow reserve; non-invasive CAD imaging; Coronary Computed Tomography Angiography; coronary CT angiography; CCTA | | [underlined: 0]
HTA: Health Technology Assessments | http://www.ohsu.edu/xd/education/library/; No update search, not updated past 2016
NHS Evidence | http://www.evidence.nhs.uk/default.aspx; Search: FFFRct; fractional flow reserve; non-invasive CAD imaging; Coronary Computed Tomography Angiography; coronary CT angiography; CCTA
VA Products - VATAP, PBM and HSR&D publications | A. http://www.hsrd.research.va.gov/research/default.cfm; B. http://www.research.va.gov/research_topics/; Search: FFFRct; fractional flow reserve; non-invasive CAD imaging; Coronary Computed Tomography Angiography; coronary CT angiography; CCTA | | 0
2. Search for systematic reviews currently under development (includes forthcoming reviews & protocols); Date Searched: 02-23-21
A. Under development | Evidence: | | Results
AHRQ topics in development (EPC Status Report) | https://www.epc-src.org/src/logon.cfm; Search: FFFRct; fractional flow reserve; non-invasive CAD imaging; Coronary Computed Tomography Angiography; coronary CT angiography; CCTA | | [underlined: 0]
PROSPERO (SR registry) | http://www.crd.york.ac.uk/PROSPERO/; Search: FFFRct; fractional flow reserve; non-invasive CAD imaging; Coronary Computed Tomography Angiography; coronary CT angiography; CCTA; Results:; Kongyong Cui. Fractional flow reserve versus angiography for guiding complete revascularization in patients with acute myocardial infarction and multivessel disease: a systematic review and meta-analysis. PROSPERO 2020 CRD42020183799 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42020183799; Donghee Han, Andrew Lin, Daniel Berman. Diagnostic performance of CT derived fractional flow reserve for the assessment of hemodynamically significant coronary artery stenosis according to coronary artery calcium score: systematic review and meta-analysis. PROSPERO 2020 CRD42020162255 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42020162255; Felicitas Vogelgesang, Maria Hanna Coenen, Sabine Schüler, Marc Dewey. Systematic review on diagnostic meta-analyses of coronary computed tomography angiography vs conventional coronary angiography. PROSPERO 2020 CRD42020162475 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42020162475; Mark Simmonds, Ruth Walker, Alexis Llewellyn, Kath Wright, Claire Rothery, Alessandro Grosso. QAngio XA 3D/QFR and CAAS vFFR imaging software for assessing coronary obstructions: a systematic review and economic evaluation. PROSPERO 2019 CRD42019154575 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42019154575 | | [underlined: 4]
DoPHER (SR Protocols) | http://eppi.ioe.ac.uk/webdatabases4/Intro.aspx?ID=9; Search: FFFRct; fractional flow reserve; non-invasive CAD imaging; Coronary Computed Tomography Angiography; coronary CT angiography; CCTA | | [underlined: 0]
Cochrane Database of Systematic Reviews: Protocols | http://www.ohsu.edu/xd/education/library/; Search: See strategy above | | [underlined: 0]

Search for primary literature; Date searched: 02-23-21
MEDLINE [Ovid MEDLINE(R) ALL 1946 to February 22, 2021]
# | Search Statement | Results
[underlined: 1] | [underlined: (FFFRct or CT-FFR* or ctFFR* or FFRct* or CT-based FFR* or FFR CT or noninvasive FFR or noninvasive fractional flow reserve or non-invasive FFR or non-invasive fractional flow reserve).mp.] | 376
[underlined: 2] | exp Fractional Flow Reserve, Myocardial/ or (Fractional Flow Reserve or FFR).mp. | 4878
[underlined: 3] | [underlined: exp Computed Tomography Angiography/] | 11297
[underlined: 4] | [underlined: (Computed Tomography Angiogra* or CCTA or coronary CT angiogra* or CT coronary angiogra*).mp.] | 21196
[underlined: 5] | [underlined: 3 or 4] | 21196
[underlined: 6] | [underlined: 2 and 5] | 663
[underlined: 7] | [underlined: 1 or 6] | 733
[underlined: 8] | Limit 7 to english language | 718
[underlined: 9] | Limit 8 to yr=”2019-Current” | 288
CCRCT [EBM Reviews - Cochrane Central Register of Controlled Trials January 2021]
# | Search Statement | Results
[underlined: 1] | [underlined: (FFFRct or CT-FFR* or ctFFR* or FFRct* or CT-based FFR* or FFR CT or noninvasive FFR or noninvasive fractional flow reserve or non-invasive FFR or non-invasive fractional flow reserve).mp.] | 48
[underlined: 2] | exp Fractional Flow Reserve, Myocardial/ or (Fractional Flow Reserve or FFR).mp. | 701
[underlined: 3] | [underlined: exp Computed Tomography Angiography/] | 0
[underlined: 4] | [underlined: (Computed Tomography Angiogra* or CCTA or coronary CT angiogra* or CT coronary angiogra*).mp.] | 1308
[underlined: 5] | [underlined: 3 or 4] | 1308
[underlined: 6] | [underlined: 2 and 5] | 61
[underlined: 7] | [underlined: 1 or 6] | 79
[underlined: 8] | Limit 7 to english language | 60
[underlined: 9] | Limit 8 to yr=”2019-Current” | 17

### APPENDIX B LIST OF EXCLUDED STUDIES

Exclude reasons: 1=Ineligible population (ie, acute coronary syndrome), 2=Ineligible intervention (ie, non HeartFlow FFRCT), 3=Ineligible comparator, 4=Ineligible outcome, 5=Ineligible setting, 6=Ineligible study design, 7=Ineligible publication type, 8=Outdated or ineligible systematic review, 9=Non-English language, 10=Unable to retrieve full text, 11=Trial included in prioritized systematic review

# | Citation | Exclude reason
1 | ACR–NASCI–SPR Practice Parameter for the Performance and Interpretation of Cardiac Computed Tomography (CT). 2017. | E2
2 | ACR–NASCI–SPR Practice Parameter for the Performance of Quantification of Cardiovascular Computed Tomography (CT) and Magnetic Resonance Imaging (MRI). 2017. | E2
3 | Al-Mallah MH, Ahmed AM. Controversies in the Use of Fractional Flow Reserve Form Computed Tomography (FFRCT) vs Coronary Angiography. Current Cardiovascular Imaging Reports. 2016;9(12). | E7
4 | Andreini D, Mushtaq S, Pontone G, Rogers C, Pepi M, Bartorelli AL. Severe in-stent restenosis missed by coronary CT angiography and accurately detected with FFR<sub>CT</sub>. The international journal of cardiovascular imaging. 2017;33(1):119–120.27581392 | E6
5 | Artzner C, Daubert M, Ehieli W, . Impact of computed tomography (CT)-derived fractional flow reserve on reader confidence for interpretation of coronary CT angiography. European Journal of Radiology. 2018;108:242–248.30396663 | E4
6 | Babakhani H, Sadeghipour P, Tashakori Beheshti A, . Diagnostic accuracy of two-dimensional coronary angiographic-derived fractional flow reserve-Preliminary results. Catheterization & Cardiovascular Interventions. 2020;27:27. | E2
7 | Ball C, Pontone G, Rabbat M. Fractional flow reserve derived from coronary computed tomography angiography datasets: the next frontier in noninvasive assessment of coronary artery disease. Biomedical Research International. 2018;2018:2680430. | E7
8 | Baumann S, Becher T, Schoepf UJ, . Fractional flow reserve derived by coronary computed tomography angiography : A sophisticated analysis method for detecting hemodynamically significant coronary stenosis. Herz. 2017;42(6):604–606.27783095 | E7
9 | Baumann S, Hirt M, Schoepf UJ, . Correlation of machine learning computed tomography-based fractional flow reserve with instantaneous wave free ratio to detect hemodynamically significant coronary stenosis. Clinical Research in Cardiology. 2020;109(6):735–745.31664509 | E2
10 | Baumann S, Lossnitzer D, Renker M, Borggrefe M, Akin I. Coronary Computed Tomography Angiography-Derived Fractional Flow Reserve Assessment: Many Roads to Reach the Same Goal. Circulation Journal. 2018;82(9):2448.30033942 | E7
11 | Baumann S, Renker M, Akin I, Borggrefe M, Schoepf UJ. FFR-Derived From Coronary CT Angiography Using Workstation-Based Approaches. Jacc: Cardiovascular Imaging. 2017;10(4):497–498.28385262 | E7
12 | Baumann S, Renker M, Hetjens S, . Comparison of coronary computed tomography angiography-derived vs invasive fractional flow reserve assessment: meta-analysis with subgroup evaluation of intermediate stenosis. Academic Radiology. 2016;23(11):1402–1411.27639627 | E8
13 | Baumann S, Renker M, Schoepf UJ, . Gender differences in the diagnostic performance of machine learning coronary CT angiography-derived fractional flow reserve -results from the MACHINE registry. European Journal of Radiology. 2019;119:108657.31521876 | E2
14 | Beg F, Rehman H, Chamsi-Pasha MA, . Association between FFR<sub>CT</sub> and instantaneous wave-free ratio (iFR) of intermediate lesions on coronary computed tomography angiography. Cardiovascular Revascularization Medicine. 2020;26:26.33229134 | E4
15 | Benton SM, Tesche C, De Cecco CN, Duguay TM, Schoepf UJ, Bayer RR, II. Noninvasive Derivation of Fractional Flow Reserve From Coronary Computed Tomographic Angiography: A Review. Journal of Thoracic Imaging. 2018;33(2):88–96.28817458 | E7
16 | Bernhardt P, Walcher T, Rottbauer W, Wohrle J. Quantification of myocardial perfusion reserve at 1.5 and 3.0 Tesla: a comparison to fractional flow reserve. International Journal of CaXIArdiovascular Imaging. 2012;28(8):2049–2056. | E2
17 | Bilbey N, Blanke P, Naoum C, Arepalli CD, Norgaard BL, Leipsic J. Potential impact of clinical use of noninvasive FFRCT on radiation dose exposure and downstream clinical event rate. Clinical Imaging. 2016;40(5):1055–1060.27388817 | E6
18 | Cademartiri F, Seitun S, Clemente A, . Myocardial blood flow quantification for evaluation of coronary artery disease by computed tomography. Cardiovascular Diagnosis & Therapy. 2017;7(2):129–150.28540209 | E7
19 | Cheruvu C, Naoum C, Blanke P, Norgaard B, Leipsic J. Beyond Stenosis With Fractional Flow Reserve Via Computed Tomography and Advanced Plaque Analyses for the Diagnosis of Lesion-Specific Ischemia. Canadian Journal of Cardiology. 2016;32(11):e1–1315. | E7
20 | Chinnaiyan KM, Akasaka T, Amano T, . Rationale, design and goals of the HeartFlow assessing diagnostic value of non-invasive FFRCT in Coronary Care (ADVANCE) registry. Journal of Cardiovascular Computed Tomography. 2017;11(1):62–67.28017291 | E7
21 | Chinnaiyan KM, Safian RD, Gallagher ML, . Clinical Use of CT-Derived Fractional Flow Reserve in the Emergency Department. Jacc: Cardiovascular Imaging. 2020;13(2 Pt 1):452–461.31326487 | E1
22 | Chung JH, Lee KE, Nam CW, . Diagnostic Performance of a Novel Method for Fractional Flow Reserve Computed from Noninvasive Computed Tomography Angiography (NOVEL-FLOW Study). American Journal of Cardiology. 2017;120(3):362–368. | E11
23 | Coenen A, Kim YH, Kruk M, . Diagnostic accuracy of a machine-learning approach to coronary computed tomographic angiography–based fractional flow reserve result from the MACHINE Consortium. Circulation: Cardiovascular Imaging. 2018;11(6):e007217.29914866 | E2
24 | Coenen A, Lubbers MM, Kurata A, . Fractional flow reserve computed from noninvasive CT angiography data: diagnostic performance of an on-site clinician-operated computational fluid dynamics algorithm. Radiology. 2015;274(3):674–683.25322342 | E2
25 | Coenen A, Rossi A, Lubbers MM, . Integrating CT Myocardial Perfusion and CT-FFR in the Work-Up of Coronary Artery Disease. JACC Cardiovascular imaging. 2017;10(7):760–770.28109933 | E2
26 | Cook CM, Petraco R, Shun-Shin MJ, . Diagnostic accuracy of computed tomography-derived fractional flow reserve a systematic review. JAMA Cardiology. 2017;2(7):803–810.28538960 | E8
27 | Danad I, Szymonifka J, Twisk JWR, . Diagnostic performance of cardiac imaging methods to diagnose ischaemia-causing coronary artery disease when directly compared with fractional flow reserve as a reference standard: A meta-analysis. European Heart Journal. 2017;38(13):991–998.27141095 | E8
28 | De Geer J, Sandstedt M, Björkholm A, . Software-based on-site estimation of fractional flow reserve using standard coronary CT angiography data. Acta Radiologica. 2016;57(10):1186–1192.26691914 | E2
29 | Deng SB, Jing XD, Wang J, . Diagnostic performance of noninvasive fractional flow reserve derived from coronary computed tomography angiography in coronary artery disease: A systematic review and meta-analysis. International journal of cardiology. 2015;184:703–709.25781722 | E8
30 | Di Jiang M, Zhang XL, Liu H, . The effect of coronary calcification on diagnostic performance of machine learning-based CT-FFR: a Chinese multicenter study. European Radiology. 2021;31(3):1482–1493.32929641 | E2
31 | Ding A, Qiu G, Lin W, . Diagnostic performance of noninvasive fractional flow reserve derived from coronary computed tomography angiography in ischemia-causing coronary stenosis: a meta-analysis. Japanese Journal of Radiology. 2016;34(12):795–808.27796727 | E8
32 | Donnelly PM, Kolossváry M, Karády J, . Experience With an On-Site Coronary Computed Tomography-Derived Fractional Flow Reserve Algorithm for the Assessment of Intermediate Coronary Stenoses. American Journal of Cardiology. 2018;121(1):9–13. | E2
33 | Douglas PS, Hoffmann U, Patel MR, . Outcomes of anatomical versus functional testing for coronary artery disease. New England Journal of Medicine. 2015;372(14):1291–1300. | E2
34 | Duguay TM, Tesche C, Vliegenthart R, . Coronary Computed Tomographic Angiography-Derived Fractional Flow Reserve Based on Machine Learning for Risk Stratification of Non-Culprit Coronary Narrowings in Patients with Acute Coronary Syndrome. American Journal of Cardiology. 2017;120(8):1260–1266. | E4
35 | Eberhard M, Nadarevic T, Cousin A, . Machine learning-based CT fractional flow reserve assessment in acute chest pain: first experience. Cardiovascular Diagnosis & Therapy. 2020;10(4):820–830.32968637 | E2
36 | Eckert J. Coronary CTA with FFRCT: a safe strategy for diagnosis of CAD? Kardiologe. 2016;10(6):336–338. | E9
37 | ECRI Institute. FFRct Software (HeartFlow, Inc.) for Evaluating Coronary Artery Disease: Product Brief. ECRI Institute;2017. | E8
38 | Eftekhari A, Min J, Achenbach S, . Fractional flow reserve derived from coronary computed tomography angiography: diagnostic performance in hypertensive and diabetic patients. European Heart Journal Cardiovascular Imaging. 2017;18(12):1351–1360.28013282 | E11
39 | Fearon WF, Lee JH. Pulling the RIPCORD: FFRCT to Improve Interpretation of Coronary CT Angiography*. JACC: Cardiovascular Imaging. 2016;9(10):1195–1197.27568112 | E7
40 | Feldmann K, Cami E, Safian RD. Planning percutaneous coronary interventions using computed tomography angiography and fractional flow reserve-derived from computed tomography: A state-of-the-art review. Catheterization and Cardiovascular Interventions. 2018. | E7
41 | Ferencik M, Lu MT, Mayrhofer T, . Non-invasive fractional flow reserve derived from coronary computed tomography angiography in patients with acute chest pain: Subgroup analysis of the ROMICAT II trial. Journal of cardiovascular computed tomography. 2019;13(4):196–202.31113728 | E1
42 | Fordyce CB, Douglas PS. Optimal non-invasive imaging test selection for the diagnosis of ischaemic heart disease. Heart. 2016;102(7):555–564.26826100 | E7
43 | Fordyce CB, Newby DE, Douglas PS. Diagnostic strategies for the evaluation of chest pain clinical implications from SCOT-HEART and PROMISE. Journal of the American College of Cardiology. 2016;67(7):843–852.26892420 | E7
44 | Fractional Flow Reserve Derived From Computed Tomography Coronary Angiography in the Assessment and Management of Stable Chest Pain. 2017. | E7
45 | Fujimoto S, Kawasaki T, Kumamaru KK, . Diagnostic performance of on-site computed CT-fractional flow reserve based on fluid structure interactions: comparison with invasive fractional flow reserve and instantaneous wave-free ratio. European Heart Journal Cardiovascular Imaging. 2018;20(3):343–352. | E2
46 | Fujimoto S, Kawasaki T, Kumamaru KK, . Diagnostic performance of on-site computed CT-fractional flow reserve based on fluid structure interactions: comparison with invasive fractional flow reserve and instantaneous wave-free ratio. European heart journal cardiovascular Imaging. 2019;20(3):343–352.30107511 | E2
47 | Gaur S, Achenbach S, Leipsic J, . Rationale and design of the HeartFlowNXT (HeartFlow analysis of coronary blood flow using CT angiography: NeXt sTeps) study. Journal of Cardiovascular Computed Tomography. 2013;7(5):279–288.24268114 | E7
48 | Gaur S, Bezerra HG, Lassen JF, . Fractional flow reserve derived from coronary CT angiography: variation of repeated analyses. Journal of Cardiovascular Computed Tomography. 2014;8(4):307–314.25151923 | E4
49 | Gaur S, Øvrehus KA, Dey D, . Coronary plaque quantification and fractional flow reserve by coronary computed tomography angiography identify ischaemia-causing lesions. European Heart Journal. 2016;37(15):1220–1227.26763790 | E4
50 | Ghekiere O, Bielen J, Leipsic J, . Correlation of FFR-derived from CT and stress perfusion CMR with invasive FFR in intermediate-grade coronary artery stenosis. The international journal of cardiovascular imaging. 2019;35(3):559–568.30284138 | E4
51 | Giannopoulos AA, Tang A, Ge Y, . Diagnostic performance of a Lattice Boltzmann-based method for CT-based fractional flow reserve. Eurointervention. 2018;13(14):1696–1704.28649949 | E2
52 | Gognieva D, Mitina Y, Gamilov T, . Noninvasive Assessment of the Fractional Flow Reserve with the CT FFRc 1D Method: Final Results of a Pilot Study. Global heart. 2021;16(1):1.33598381 | E2
53 | Guo W, Lin Y, Taniguchi A, . Prospective comparison of integrated on-site CT-fractional flow reserve and static CT perfusion with coronary CT angiography for detection of flow-limiting coronary stenosis. European Radiology. 2021;06:06. | E2
54 | Hachamovitch R, Nutter B, Hlatky MA, . Patient management after noninvasive cardiac imaging results from SPARC (Study of myocardial perfusion and coronary anatomy imaging roles in coronary artery disease). Journal of the American College of Cardiology. 2012;59(5):462–474.22281249 | E2
55 | Hecht HS, Narula J, Fearon WF. Fractional flow reserve and coronary computed tomographic angiography: a review and critical analysis. Circulation Research. 2016;119(2):300–316.27390333 | E7
56 | Hoffmann U, Ferencik M, Udelson JE, . Prognostic Value of Noninvasive Cardiovascular Testing in Patients With Stable Chest Pain: Insights From the PROMISE Trial (Prospective Multicenter Imaging Study for Evaluation of Chest Pain). Circulation. 2017;135(24):2320–2332.28389572 | E2
57 | Hu X, Yang M, Han L, Du Y. Diagnostic performance of machine-learning-based computed fractional flow reserve (FFR) derived from coronary computed tomography angiography for the assessment of myocardial ischemia verified by invasive FFR. International Journal of Cardiovascular Imaging. 2018;34(12):1987–1996. | E2
58 | Hulten EA. Does FFRCT have proven utility as a gatekeeper prior to invasive angiography? Journal of Nuclear Cardiology. 2017;24(5):1619–1625.28681339 | E7
59 | Hulten E, Blankstein R, Di Carli MF. The value of noninvasive computed tomography derived fractional flow reserve in our current approach to the evaluation of coronary artery stenosis. Current Opinion in Cardiology. 2016;31(6):670–676. | E7
60 | Hulten E, Di Carli MF. FFRCT: Solid PLATFORM or thin ice? Journal of the American College of Cardiology. 2015;66(21):2324–2328.26475206 | E7
61 | Hwang D, Lee JM, Koo BK. Physiologic assessment of coronary artery disease: Focus on fractional flow reserve. Korean Journal of Radiology. 2016;17(3):307–320.27134520 | E7
62 | Ihdayhid AR, Sakaguchi T, Linde JJ, . Performance of computed tomography-derived fractional flow reserve using reduced-order modelling and static computed tomography stress myocardial perfusion imaging for detection of haemodynamically significant coronary stenosis. European Heart Journal Cardiovascular Imaging. 2018;19(11):1234–1243.30137268 | E2
63 | Karady J, Mayrhofer T, Ivanov A, . Cost-effectiveness Analysis of Anatomic vs Functional Index Testing in Patients With Low-Risk Stable Chest Pain. JAMA Network Open. 2020;3(12):e2028312.33315111 | E6
64 | Kato E, Fujimoto S, Kumamaru KK, . Adjustment of CT-fractional flow reserve based on fluid-structure interaction underestimation to minimize 1-year cardiac events. Heart & Vessels. 2020;35(2):162–169.31392411 | E2
65 | Kawaji T, Shiomi H, Morishita H, . Feasibility and diagnostic performance of fractional flow reserve measurement derived from coronary computed tomography angiography in real clinical practice. International Journal of Cardiovascular Imaging. 2017;33(2):271–281. | E11
66 | Kawashima H, Pompilio G, Andreini D, . Safety and feasibility evaluation of planning and execution of surgical revascularisation solely based on coronary CTA and FFR<sub>CT</sub> in patients with complex coronary artery disease: study protocol of the FASTTRACK CABG study. BMJ Open. 2020;10(12):e038152. | E7
67 | Kerut EK, Turner M. Fractional flow reserve-CT assessment of coronary stenosis. Echocardiography. 2018;35(5):730–732.29569282 | E7
68 | Kim KH, Doh JH, Koo BK, . A novel noninvasive technology for treatment planning using virtual coronary stenting and computed tomography-derived computed fractional flow reserve. JACC Cardiovascular Interventions. 2014;7(1):72–78.24332418 | E11
69 | Kim SH, Kang SH, Chung WY, . Validation of the diagnostic performance of ‘HeartMedi V.1.0’, a novel CT-derived fractional flow reserve measurement, for patients with coronary artery disease: a study protocol. BMJ Open. 2020;10(7):e037780. | E2
70 | Kim HJ, Vignon-Clementel IE, Coogan JS, Figueroa CA, Jansen KE, Taylor CA. Patient-specific modeling of blood flow and pressure in human coronary arteries. Annals of Biomedical Engineering. 2010;38(10):3195–3209.20559732 | E2
71 | Kishi S, Giannopoulos AA, Tang A, . Fractional flow reserve estimated at coronary CT angiography in intermediate lesions: comparison of diagnostic accuracy of different methods to determine coronary flow distribution. Radiology. 2018;287(1):76–84.29156145 | E2
72 | Kitabata H, Leipsic J, Patel MR, . Incidence and predictors of lesion-specific ischemia by FFRCT: Learnings from the international ADVANCE registry. Journal of Cardiovascular Computed Tomography. 2018;12(2):95–100.29422416 | E4
73 | Knaapen P. FFR<sub>CT</sub> Versus SPECT to Diagnose Coronary Artery Disease: Toward a Tailored Approach. Jacc: Cardiovascular Imaging. 2018;11(11):1651–1653.30409328 | E7
74 | Ko BS, Cameron JD, Munnur RK, . Noninvasive CT-Derived FFR Based on Structural and Fluid Analysis: A Comparison With Invasive FFR for Detection of Functionally Significant Stenosis. JACC: Cardiovascular Imaging. 2017;10(6):663–673.27771399 | E2
75 | Ko BS, Wong DT, Norgaard BL, . Diagnostic Performance of Transluminal Attenuation Gradient and Noninvasive Fractional Flow Reserve Derived from 320-Detector Row CT Angiography to Diagnose Hemodynamically Significant Coronary Stenosis: An NXT Substudy. Radiology. 2016;279(1):75–83.26444662 | E2
76 | Kolossváry M, Szilveszter B, Merkely B, Maurovich-Horvat P. Plaque imaging with CT-A comprehensive review on coronary CT angiography based risk assessment. Cardiovascular Diagnosis and Therapy. 2017;7(5):489–506.29255692 | E7
77 | Koo B-K, Erglis A, Doh J-H, . Diagnosis of ischemia-causing coronary stenoses by noninvasive fractional flow reserve computed from coronary computed tomographic angiograms: results from the prospective multicenter DISCOVER-FLOW (Diagnosis of Ischemia-Causing Stenoses Obtained Via Noninvasive Fractional Flow Reserve) Study. Journal of the American College of Cardiology. 2011;58(19):1989–1997.22032711 | E11
78 | Krievins D, Zellans E, Latkovskis G, . Diagnosis and management of silent coronary ischemia in patients undergoing carotid endarterectomy. Journal of Vascular Surgery. 2021;73(2):533–541.32623107 | E1
79 | Krievins D, Zellans E, Latkovskis G, . Pre-operative Diagnosis of Silent Coronary Ischaemia May Reduce Post-operative Death and Myocardial Infarction and Improve Survival of Patients Undergoing Lower Extremity Surgical Revascularisation. European Journal of Vascular & Endovascular Surgery. 2020;60(3):411–420.32709470 | E1
80 | Kueh SH, Boroditsky M, Leipsic J. Fractional flow reserve computed tomography in the evaluation of coronary artery disease. Cardiovascular Diagnosis and Therapy. 2017;7(5):463–474.29255690 | E7
81 | Kumamaru KK, Fujimoto S, Otsuka Y, . Diagnostic accuracy of 3D deep-learning-based fully automated estimation of patient-level minimum fractional flow reserve from coronary computed tomography angiography. European heart journal cardiovascular Imaging. 2020;21(4):437–445.31230076 | E2
82 | Kurata A, Fukuyama N, Hirai K, . On-Site Computed Tomography-Derived Fractional Flow Reserve Using a Machine-Learning Algorithm - Clinical Effectiveness in a Retrospective Multicenter Cohort. Circulation Journal. 2019;83(7):1563–1571.31178524 | E2
83 | Leber WA. Is FFR-CT a “game changer” in the diagnostic management of stable coronary artery disease? Herz. 2016;41(5):398–404.27393032 | E7
84 | Lee JH, Hartaigh BÓ, Han D, Rizvi A, Lin FY, Min JK. Fractional flow reserve measurement by computed tomography: An alternative to the stress test. Interventional Cardiology Review. 2016;11(2):105–109.29588715 | E7
85 | Leipsic JA, Koweek LH. CT fractional flow reserve for stable coronary artery disease: The ongoing journey. Radiology. 2018;287(1):85–86.29558312 | E7
86 | Leipsic J, Weir-McCall J, Blanke P. FFR<sub>CT</sub> for Complex Coronary Artery Disease Treatment Planning: New Opportunities. Interventional Cardiology. 2018;13(3):126–128.30443268 | E7
87 | Li Y, Qiu H, Hou Z, . Additional value of deep learning computed tomographic angiography-based fractional flow reserve in detecting coronary stenosis and predicting outcomes. Acta Radiologica. 2021:284185120983977.33423530 | E2
88 | Li Y, Yu M, Dai X, . Detection of Hemodynamically Significant Coronary Stenosis: CT Myocardial Perfusion versus Machine Learning CT Fractional Flow Reserve. Radiology. 2019;293(2):305–314.31549943 | E2
89 | Li Z, Zhang J, Xu L, . Diagnostic Accuracy of a Fast Computational Approach to Derive Fractional Flow Reserve From Coronary CT Angiography. Jacc: Cardiovascular Imaging. 2020;13(1 Pt 1):172–175.31542542 | E2
90 | Liu X, Peng C, Xia Y, . Hemodynamics analysis of the serial stenotic coronary arteries. BioMedical Engineering Online. 2017;16(1). | E2
91 | Liu X, Wang Y, Zhang H, . Evaluation of fractional flow reserve in patients with stable angina: can CT compete with angiography? European Radiology. 2019;29(7):3669–3677.30887203 | E2
92 | Lobanova I, Qureshi AI. Editorial to 1-year outcomes of FFRCT-guided care in patients with suspected coronary disease. Cardiovascular Diagnosis and Therapy. 2017;7:S115–S118.28748162 | E7
93 | Lossnitzer D, Chandra L, Rutsch M, . Additional Value of Machine-Learning Computed Tomographic Angiography-Based Fractional Flow Reserve Compared to Standard Computed Tomographic Angiography. Journal of Clinical Medicine. 2020;9(3):03. | E2
94 | Lu MT, Ferencik M, Roberts RS, . Noninvasive FFR derived from coronary CT angiography: management and outcomes in the PROMISE trial. JACC: Cardiovascular Imaging. 2017;10(11):1350–1358.28412436 | E4
95 | Mahmoudi M, Nicholas Z, Nuttall J, . Fractional Flow Reserve Derived from Computed Tomography Coronary Angiography in the Assessment and Management of Stable Chest Pain: Rationale and Design of the FORECAST Trial. Cardiovascular Revascularization Medicine. 2020;21(7):890–896.31932171 | E7
96 | Mangla A, Oliveros E, Williams KA, Sr., Kalra DK. Cardiac Imaging in the Diagnosis of Coronary Artery Disease. Current Problems in Cardiology. 2017;42(10):316–366.28870377 | E7
97 | Mastrodicasa D, Albrecht MH, Schoepf UJ, . Artificial intelligence machine learning-based coronary CT fractional flow reserve (CT-FFR<sub>ML</sub>): Impact of iterative and filtered back projection reconstruction techniques. Journal of Cardiovascular Computed Tomography. 2018. | E3
98 | Mathew RC, Gottbrecht M, Salerno M. Computed Tomography Fractional Flow Reserve to Guide Coronary Angiography and Intervention. Interventional Cardiology Clinics. 2018;7(3):345–354.29983146 | E7
99 | Meier D, Skalidis I, De Bruyne B, . Ability of FFR-CT to detect the absence of hemodynamically significant lesions in patients with high-risk NSTE-ACS admitted in the emergency department with chest pain, study design and rationale. International Journal of Cardiology Heart & Vasculature. 2020;27:100496.32181323 | E7
100 | Michail M, Ihdayhid AR, Comella A, . Feasibility and Validity of Computed Tomography-Derived Fractional Flow Reserve in Patients With Severe Aortic Stenosis: The CAST-FFR Study. Circulation: Cardiovascular Interventions. 2021;14(1):e009586.33322917 | E1
101 | Min JK, Leipsic J, Pencina MJ, . Diagnostic accuracy of fractional flow reserve from anatomic CT angiography. JAMA. 2012;308(12):1237–1245.22922562 | E11
102 | Min JK, Taylor CA, Achenbach S, . Noninvasive fractional flow reserve derived from coronary CT angiography clinical data and scientific principles. JACC: Cardiovascular Imaging. 2015;8(10):1209–1222.26481846 | E7
103 | Miyajima K, Motoyama S, Sarai M, . On-site assessment of computed tomography-derived fractional flow reserve in comparison with myocardial perfusion imaging and invasive fractional flow reserve. Heart & Vessels. 2020;35(10):1331–1340.32350637 | E2
104 | Miyoshi T, Osawa K, Ito H, . Non-invasive computed fractional flow reserve from computed tomography (CT) for diagnosing coronary artery disease - Japanese results from NXT trial (Analysis of Coronary Blood Flow Using CT Angiography: Next Steps). Circulation journal : official journal of the Japanese Circulation Society. 2015;79(2):406–412.25452201 | E11
105 | Mordi IR, Badar AA, John Irving R, Weir-McCall JR, Houston JG, Lang CC. Efficacy of noninvasive cardiac imaging tests in diagnosis and management of stable coronary artery disease. Vascular Health and Risk Management. 2017;13:427–437.29200864 | E7
106 | Nakanishi R, Budoff MJ. Noninvasive FFR derived from coronary CT angiography in the management of coronary artery disease: Technology and clinical update. Vascular Health and Risk Management. 2016;12:269–278.27382296 | E7
107 | Nakazato R, Park HB, Gransar H, . Additive diagnostic value of atherosclerotic plaque characteristics to non-invasive FFR for identification of lesions causing ischaemia: results from a prospective international multicentre trial. EuroIntervention. 2016;12(4):473–481.26348673 | E2
108 | Neglia D, Rovai D, Caselli C, . Detection of significant coronary artery disease by noninvasive anatomical and functional imaging. Circulation Cardiovascular imaging. 2015;8(3). | E2
109 | NICE. HeartFlow FFRCT for estimating fractional flow reserve from coronary CT angiography. 2017. | E8
110 | NICE. HeartFlow FFRCT for estimating fractional flow reserve from coronary CT angiography: Tools and resources. 2017. | E7
111 | NICE. QAngio XA 3D/QFR imaging software for assessing coronary obstructions - medtech innovation briefing (MIB146). 2018. | E2
112 | Noninvasive computed fractional flow reserve from computed tomography (FFRCT) for coronary artery disease. Centre for Reviews and Dissemination. 2017. | E10
113 | Norgaard BL, Botker HE, Jensen JM. Recent controversy regarding the accuracy of CT-FFR. The truth is out there. Journal of Cardiovascular Computed Tomography. 2018;12(1):e1.29191632 | E7
114 | Norgaard BL, Gaur S, Leipsic J, . Influence of Coronary Calcification on the Diagnostic Performance of CT Angiography Derived FFR in Coronary Artery Disease: A Substudy of the NXT Trial. JACC Cardiovascular imaging. 2015;8(9):1045–1055.26298072 | E11
115 | Nørgaard BL, Jensen JM, Blanke P, Sand NP, Rabbat M, Leipsic J. Coronary CT Angiography Derived Fractional Flow Reserve: The Game Changer in Noninvasive Testing. Current Cardiology Reports. 2017;19(11). | E7
116 | Norgaard BL, Leipsic J, Gaur S, . Diagnostic performance of noninvasive fractional flow reserve derived from coronary computed tomography angiography in suspected coronary artery disease: the NXT trial (Analysis of coronary blood flow using CT angiography: next steps). Journal of the American College of Cardiology. 2014;63(12):1145–1155.24486266 | E11
117 | Norgaard BL, Terkelsen CJ, Mathiassen ON, . Coronary CT Angiographic and Flow Reserve-Guided Management of Patients With Stable Ischemic Heart Disease. Journal of the American College of Cardiology. 2018;72(18):2123–2134.30153968 | E3
118 | Nous F BRLMYYMPBTAJKMKBGTNK. Incremental value of on-site computed tomography-derived fractional flow reserve for the diagnosis and management strategy of obstructive coronary artery disease in the randomized CRESCENT trials. European heart journal. 3782;40. | E2
119 | Nous FMA, Budde RPJ, Lubbers MM, . Impact of machine-learning CT-derived fractional flow reserve for the diagnosis and management of coronary artery disease in the randomized CRESCENT trials. European Radiology. 2020;30(7):3692–3701.32166492 | E2
120 | Nous FMA, Coenen A, Boersma E, . Comparison of the diagnostic performance of coronary computed tomography angiography-derived fractional flow reserve in patients with versus without diabetes mellitus (from the MACHINE Consortium). American Journal of Cardiology. 2019;123(4):537–543. | E2
121 | Osawa K, Miyoshi T, Miki T, . Coronary lesion characteristics with mismatch between fractional flow reserve derived from CT and invasive catheterization in clinical practice. Heart & Vessels. 2017;32(4):390–398.27624311 | E11
122 | Otake H, Taylor CA, Matsuo H, Tanaka N, Akasaka T. Noninvasive Fractional Flow Reserve Derived From Coronary Computed Tomography Angiography - Is This Just Another New Diagnostic Test or the Long-Awaited Game Changer? Circulation Journal. 2017;81(8):1085–1093.28413187 | E7
123 | Packard RR, Li D, Budoff MJ, Karlsberg RP. Fractional flow reserve by computerized tomography and subsequent coronary revascularization. European Heart Journal Cardiovascular Imaging. 2017;18(2):145–152.27469588 | E4
124 | Panchal HB, Veeranki SP, Bhatheja S, . Fractional flow reserve using computed tomography for assessing coronary artery disease: a meta-analysis. Journal of Cardiovascular Medicine. 2016;17(9):694–700.27472038 | E8
125 | Park HB, Jang Y, Arsanjani R, . Diagnostic Accuracy of a Novel On-site Virtual Fractional Flow Reserve Parallel Computing System. Yonsei Medical Journal. 2020;61(2):137–144.31997622 | E2
126 | Patel AR, Maffessanti F, Patel MB, . Hemodynamic impact of coronary stenosis using computed tomography: comparison between noninvasive fractional flow reserve and 3D fusion of coronary angiography with stress myocardial perfusion. The international journal of cardiovascular imaging. 2019;35(9):1733–1743.31073698 | E4
127 | Podgorsak AR, Sommer KN, Reddy A, . Initial evaluation of a convolutional neural network used for noninvasive assessment of coronary artery disease severity from coronary computed tomography angiography data. Medical Physics. 2020;47(9):3996–4004.32562286 | E2
128 | Pontone G, Andreini D, Guaricci AI, . Rationale and design of the PERFECTION (comparison between stress cardiac computed tomography PERfusion versus Fractional flow rEserve measured by Computed Tomography angiography In the evaluation of suspected cOroNary artery disease) prospective study. Journal of Cardiovascular Computed Tomography. 2016;10(4):330–334.27050025 | E7
129 | Pontone G, Carita P, Verdecchia M, . Fractional flow reserve: Lessons from PLATFORM and future perspectives. Minerva Cardioangiologica. 2017;65(3):235–251.27901333 | E7
130 | Pontone G, Muscogiuri G, Andreini D, . The New Frontier of Cardiac Computed Tomography Angiography: Fractional Flow Reserve and Stress Myocardial Perfusion. Current Treatment Options in Cardiovascular Medicine. 2016;18(12). | E7
131 | Qiao HY, Li JH, Schoepf UJ, . Prognostic implication of CT-FFR based functional SYNTAX score in patients with de novo three-vessel disease. European heart journal cardiovascular Imaging. 2020;13:13. | E2
132 | Qiao HY, Tang CX, Schoepf UJ, . Impact of machine learning-based coronary computed tomography angiography fractional flow reserve on treatment decisions and clinical outcomes in patients with suspected coronary artery disease. European Radiology. 2020;30(11):5841–5851.32462444 | E2
133 | Rabbat M, Kauh B, Pontone G, Norgaard B, Lopez J, Mathew V. Fractional flow reserve derived from coronary computed tomography safely reduces invasive coronary angiography rates and cost in patients with stable coronary artery disease. Journal of the American College of Cardiology. 2017;69(11 Supplement):72. | E7
134 | Raja J, Seitz MP, Yedlapati N, Khouzam RN. Can Computed Fractional Flow Reserve Coronary CT Angiography (FFRCT) Offer an Accurate Noninvasive Comparison to Invasive Coronary Angiography (ICA)? “The Noninvasive CATH.” A Comprehensive Review. Current Problems in Cardiology. 2021;46(3):100642.32624193 | E7
135 | Rajani R, Modi B, Ntalas I, Curzen N. Non-invasive fractional flow reserve using computed tomographic angiography: Where are we now and where are we going? Heart. 2017;103(15):1216–1222.28559426 | E7
136 | Rajani R, Webb J, Marciniak A, Preston R. Comparative efficacy testing - fractional flow reserve by coronary computed tomography for the evaluation of patients with stable chest pain. International Journal of Cardiology. 2015;183:173–177.25666127 | E4
137 | Renker M, Schoepf UJ, Becher T, . Computed tomography in patients with chronic stable angina: Fractional flow reserve measurement. Herz. 2017;42(1):51–57.27255115 | E9
138 | Renker M, Schoepf UJ, Wang R, . Comparison of diagnostic value of a novel noninvasive coronary computed tomography angiography method versus standard coronary angiography for assessing fractional flow reserve. American Journal of Cardiology. 2014;114(9):1303–1308. | E2
139 | Ronnow Sand NP, Nissen L, Winther S, . Prediction of Coronary Revascularization in Stable Angina: Comparison of FFR<sub>CT</sub> With CMR Stress Perfusion Imaging. Jacc: Cardiovascular Imaging. 2020;13(4):994–1004.31422146 | E4
140 | Roobottom C. Radical changes to the investigation of stable chest pain following the 2016 NICE update. British Journal of Radiology. 2018;91(1087). | E10
141 | Ropp A, White C. Current and Future Applications of Coronary CT Angiography with and Without FFR in the Emergency Room. Current Cardiovascular Imaging Reports. 2016;9(11). | E7
142 | Rother J, Moshage M, Dey D, . Comparison of invasively measured FFR with FFR derived from coronary CT angiography for detection of lesion-specific ischemia: Results from a PC-based prototype algorithm. Journal of Cardiovascular Computed Tomography. 2018;12(2):101–107.29409717 | E2
143 | Sand NPR, Veien KT, Nielsen SS, . Prospective comparison of FFR derived from coronary CT angiography with SPECT perfusion imaging in stable coronary artery disease: the ReASSESS Study. JACC: Cardiovascular Imaging. 2018;11(11):1640–1650.29909103 | E4
144 | Schuijf JD, Ko BS, Di Carli MF, . Fractional flow reserve and myocardial perfusion by computed tomography: A guide to clinical application. European Heart Journal Cardiovascular Imaging. 2018;19(2):127–135.29045612 | E7
145 | Sevag Packard RR, Karlsberg RP. Integrating FFRCT Into Routine Clinical Practice: A Solid PLATFORM or Slippery Slope?*. Journal of the American College of Cardiology. 2016;68(5):446–449.27470450 | E7
146 | Sigurdsson G. Improved Precision of Initial Chest Pain Evaluation With Fractional Flow Reserve Computed Tomography. Journal of the American Heart Association. 2017;6(8):22. | E7
147 | Shah AB, Kirsch J, Bolen MA, . ACR Appropriateness Criteria((R)) Chronic Chest Pain-Noncardiac Etiology Unlikely-Low to Intermediate Probability of Coronary Artery Disease. Journal of the American College of Radiology. 2018;15(11S):S283–S290.30392597 | E7
148 | Shi C, Zhang D, Cao K, . A study of noninvasive fractional flow reserve derived from a simplified method based on coronary computed tomography angiography in suspected coronary artery disease. Biomedical Engineering Online. 2017;16(1):43.28407768 | E2
149 | Siontis GC, Mavridis D, Greenwood JP, . Outcomes of non-invasive diagnostic modalities for the detection of coronary artery disease: network meta-analysis of diagnostic randomised controlled trials. BMJ. 2018;360:k504.29467161 | E2
150 | Skelly AC, Hashimoto R, Buckley DI, . Noninvasive Testing for Coronary Artery Disease. In: AHRQ Comparative Effectiveness Reviews. Rockville (MD): Agency for Healthcare Research and Quality (US); 2016. | E2
151 | Takagi H, Ishikawa Y, Orii M, . Optimized interpretation of fractional flow reserve derived from computed tomography: Comparison of three interpretation methods. Journal of Cardiovascular Computed Tomography. 2018. | E3
152 | Takahashi K KNTMCPCCCMROMKHRJADDTSP. TCT-326 Diagnostic Performance of Angiography-Based Quantitative Flow Ratio With Respect to Fractional Flow Reserve Derived From Computed Tomography Angiography: insight From the SYNTAX III Trial. Journal of the American College of Cardiology.74(13):B324–. | E4
153 | Tan XW, Zheng Q, Shi L, . Combined diagnostic performance of coronary computed tomography angiography and computed tomography derived fractional flow reserve for the evaluation of myocardial ischemia: A meta-analysis. International Journal of Cardiology. 2017;236:100–106.28262348 | E3
154 | Tan Y, Litt H. High-risk plaque features predict ischemia in acute chest pain-direct comparison to non-invasive FFR. Journal of cardiovascular computed tomography. 2017;Conference: 12th annual scientific meeting of the society of cardiovascular computed tomography. United states. 11(4 Supplement 1):S76-S77. | E4
155 | Tanaka K, Bezerra HG, Gaur S, . Comparison between non-invasive (coronary computed tomography angiography derived) and invasive-fractional flow reserve in patients with serial stenoses within one coronary artery: A NXT Trial substudy. Annals of Biomedical Engineering. 2016;44(2):580–589.26329923 | E4
156 | Tang CX, Liu CY, Lu MJ, . CT FFR for Ischemia-Specific CAD With a New Computational Fluid Dynamics Algorithm: A Chinese Multicenter Study. Jacc: Cardiovascular Imaging. 2020;13(4):980–990.31422138 | E2
157 | Tesche C, De Cecco CN, Albrecht MH, . Coronary CT angiography-derived fractional flow reserve. Radiology. 2017;285(1):17–33.28926310 | E7
158 | Tesche C, De Cecco CN, Baumann S, . Coronary CT Angiography-derived Fractional Flow Reserve: Machine Learning Algorithm versus Computational Fluid Dynamics Modeling. Radiology. 2018;288(1):64–72.29634438 | E3
159 | Tesche C, Vliegenthart R, Duguay TM, . Coronary Computed Tomographic Angiography-Derived Fractional Flow Reserve for Therapeutic Decision Making. American Journal of Cardiology. 2017;120(12):2121–2127. | E2
160 | Thompson AG, Raju R, Blanke P, . Diagnostic accuracy and discrimination of ischemia by fractional flow reserve CT using a clinical use rule: results from the Determination of Fractional Flow Reserve by Anatomic Computed Tomographic Angiography study. Journal of Cardiovascular Computed Tomography. 2015;9(2):120–128.25819194 | E2
161 | van Assen M, De Cecco CN, Eid M, . Prognostic value of CT myocardial perfusion imaging and CT-derived fractional flow reserve for major adverse cardiac events in patients with coronary artery disease. Journal of cardiovascular computed tomography. 2019;13(3):26–33.30796003 | E2
162 | Varga-Szemes A, Schoepf UJ, Maurovich-Horvat P, . Coronary plaque assessment of Vasodilative capacity by CT angiography effectively estimates fractional flow reserve. International Journal of Cardiology. 2021;30:30. | E2
163 | Wang ZQ, Zhou YJ, Zhao YX, . Diagnostic accuracy of a deep learning approach to calculate FFR from coronary CT angiography. Journal of Geriatric Cardiology. 2019;16(1):42–48.30800150 | E2
164 | Wardziak L, Kruk M, Pleban W, . Coronary CTA enhanced with CTA based FFR analysis provides higher diagnostic value than invasive coronary angiography in patients with intermediate coronary stenosis. Journal of Cardiovascular Computed Tomography. 2019;13(1):62–67.30309764 | E2
165 | Wu W, Pan DR, Foin N, . Noninvasive fractional flow reserve derived from coronary computed tomography angiography for identification of ischemic lesions: A systematic review and meta-analysis. Scientific Reports. 2016;6. | E8
166 | Xia G, Fan D, Yao X, Guan G, Wang J. Diagnostic efficacy of fractional flow reserve with coronary angiography in dual-source computed tomography scanner. Acta Cardiologica. 2018;73(1):76–83.28830299 | E11
167 | Xie X, Zheng M, Wen D, Li Y, Xie S. A new CFD based non-invasive method for functional diagnosis of coronary stenosis. Biomedical Engineering Online. 2018;17(1):36.29566702 | E2
168 | Xu PP, Li JH, Zhou F, . The influence of image quality on diagnostic performance of a machine learning-based fractional flow reserve derived from coronary CT angiography. European Radiology. 2020;30(5):2525–2534.32006167 | E2
169 | Yang DH, Kang SJ, Koo HJ, . Incremental Value of Subtended Myocardial Mass for Identifying FFR-Verified Ischemia Using Quantitative CT Angiography: Comparison With Quantitative Coronary Angiography and CT-FFR. Jacc: Cardiovascular Imaging. 2018;12:12. | E2
170 | Yang DH, Kim YH, Roh JH, . Diagnostic performance of on-site CT-derived fractional flow reserve versus CT perfusion. European heart journal cardiovascular Imaging. 2017;18(4):432–440.27354345 | E2
171 | Yang J, Shan D, Dong M, . The effect of on-site CT-derived fractional flow reserve on the management of decision making for patients with stable chest pain (TARGET trial): objective, rationale, and design. Trials [Electronic Resource]. 2020;21(1):728. | E2
172 | Yang L, Xu L, He J, . Diagnostic performance of a fast non-invasive fractional flow reserve derived from coronary CT angiography: an initial validation study. Clinical Radiology. 2019;74(12):973.e971–973.e976. | E2
173 | Yoshikawa Y, Nakamoto M, Nakamura M, . On-site evaluation of CT-based fractional flow reserve using simple boundary conditions for computational fluid dynamics. The international journal of cardiovascular imaging. 2020;36(2):337–346.31628575 | E2
174 | Zhou F, Wang YN, Schoepf UJ, . Diagnostic Performance of Machine Learning Based CT-FFR in Detecting Ischemia in Myocardial Bridging and Concomitant Proximal Atherosclerotic Disease. Canadian Journal of Cardiology. 2019;35(11):1523–1533. | E2
175 | Zhuang B, Wang S, Zhao S, Lu M. Computed tomography angiography-derived fractional flow reserve (CT-FFR) for the detection of myocardial ischemia with invasive fractional flow reserve as reference: systematic review and meta-analysis. Eur Radiol. 2020;30(2):712–725.31696294 | E2
176 | Zarins CK, Taylor CA, Min JK. Computed Fractional Flow Reserve (FFTCT) Derived from Coronary CT Angiography. Journal of Cardiovascular Translational Research. 2013;6(5):708–714.23934536 | E7

### APPENDIX C EVIDENCE TABLES

#### DATA ABSTRACTION OF INCLUDED SYSTEMATIC REVIEWS

#### DATA ABSTRACTION OF INCLUDED PRIMARY STUDIES

##### Data Abstraction of Primary Studies Evaluating Diagnostic Accuracy of HeartFlow FFR_CT_

##### Data Abstraction of Primary Studies Evaluating Clinical or Therapeutic Outcomes

###### Study Characteristics

###### Outcomes

#### QUALITY ASSESSMENT OF INCLUDED STUDIES

##### Quality Assessment of Systematic Reviews using ROBIS-SR

##### Quality Assessment of Diagnostic Accuracy Studies Using QUADAS-2

##### Quality Assessment of Cohort Studies Using ROBINS-I

##### Quality Assessment of Case Series Using Murad et al

#### STRENGTH OF EVIDENCE OF INCLUDED STUDIES

### APPENDIX D ONGOING HEARTFLOW FFR_CT_ STUDIES

PI or Researcher Institution | Study Title Identifier | Summary | Status Estimated completion
David Brown, MD; Baylor Research Institute | HeartFlow (AFFECTS); NCT02973126 (https://clinicaltrials.gov/show/NCT02973126) | The overall objective of the AFFECTS Study is to assess agreement between SPECT and FFR_CT_ in identifying vessel-specific, hemodynamically significant CAD in patients scheduled for invasive coronary angiography (ICA) based on abnormal SPECT myocardial perfusion scans. In particular, the study will evaluate the ability of FFR_CT_ to correctly rule out hemodynamically significant CAD in patients with non-significant CAD or normal coronary arteries who had positive SPECT scans. | Recruiting; December 2021
Pamela S Douglas; HeartFlow, Inc. | The PRECISE Protocol: Prospective Randomized Trial of the Optimal Evaluation of Cardiac Symptoms and Revascularization (PRECISE); NCT03702244 (https://clinicaltrials.gov/show/NCT03702244) | PRECISE will evaluate whether a precision evaluation strategy that combines contemporary risk stratification using the PROMISE Risk Tool with functional and anatomic noninvasive evaluation with CCTA with selective FFR_CT_ can improve outcomes over usual care in stable chest pain patients while safely deferring further testing in low-risk patients and reducing cost overall | Not yet recruiting; Estimated Completion: April 2022
Bernard De Bruyne, MD, PhD; Onze Lieve Vrouw Hospital | Precise Percutaneous Coronary Intervention Plan (P3) Study; NCT03782688 (https://clinicaltrials.gov/ct2/show/NCT03782688?term=heartflow&recrs=abdf&draw=1&rank=2) | The Precise Percutaneous Coronary Intervention (PCI) Plan Study is an investigator-initiated, international and multicenter study of patients with an indication for PCI aiming at assessing the agreement and accuracy of the HeartFlow Planner with invasive FFR as a reference. | Recruiting; January 15, 2021
Hiromasa Otake, MD; Kobe University | Evaluation of Fractional Flow Reserve Calculated by Computed Tomography Coronary Angiography in Patients Undergoing TAVR (FORTUNA); NCT03665389 (https://clinicaltrials.gov/ct2/show/NCT03665389?term=heartflow&recrs=abdf&draw=1&rank=6https://clinicaltrials.gov/ct2/show/NCT03665389?term=heartflow&recrs=abdf&draw=1&rank=6) | The objective of this study is to evaluate the relationship between FFR derived from FFR_CT_ before transcatheter aortic valve replacement (TAVR) and FFR after TAVR to investigate whether FFR_CT_ is useful for evaluating myocardial ischemia of severe AS. | Not yet recruiting; March 31, 2022
Patrick W Serruys, Prof. dr.; National University of Ireland | Safety and Feasibility Evaluation of Planning and Execution of Surgical Revascularization Solely Based on Coronary CTA and FFRCT in Patients With Complex Coronary Artery Disease (FASTTRACK CABG); NCT04142021 | Prospective, multicenter, single-arm study to “assess the feasibility of [CTA] and [FFR_CT_] to replace invasive coronary angiography (ICA) as a surgical guidance method for planning and execution of coronary artery bypass graft (CABG) in patients with 3-vessel disease with or without left main disease.” Primary endpoint: CABG feasibility by CTA alone and occlusion rate for CTA-guided grafts at 1-month follow-up. | Recruiting; December 31, 2021
Nicolas van Mieghem; Erasmus Medical Center | The Heartflow Coronary Disease Progression Evaluation Study (THRONE); NCT04052256 | Prospective, single-center, single-arm study to “evaluate disease progression in intermediate lesions (invasive FFR 0.81–0.90 at baseline) using FFR_CT_ at 2 years and determine whether CT characteristics may help to identify lesions that are more susceptible for FFR decline.” | Recruiting; October 2023

Abbreviations: CABG= coronary artery bypass grafting; CAD=coronary artery disease; CCTA=coronary computed tomography angiography; FFR=fraction flow reserve; FFR_CT_=fractional flow reserve using computed tomography; ICA=invasive coronary angiography; PCI=percutaneous coronary intervention; SPECT=single-photon emission computed tomography; TAVR=transcatheter aortic valve replacement

### APPENDIX E DISPOSITION OF PEER REVIEWER COMMENTS

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | None
2 | 2 | Yes | None
3 | 3 | Yes | None
4 | 4 | Yes | None
5 | 5 | Yes | None
6 | 6 | Yes | None
Is there any indication of bias in our synthesis of the evidence?
7 | 1 | No | None
8 | 2 | No | None
9 | 3 | No | None
10 | 4 | No | None
11 | 5 | No | None
12 | 6 | No | None
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
13 | 1 | No | None
14 | 2 | No | None
15 | 3 | No | None
16 | 4 | No | None
17 | 5 | Yes - JAMA Netw Open. 2020;3(12):e2028312. | We formally excluded this study as it uses data from patients that have not received HeartFlow. As the implications and validity of this model are unclear, we have not discussed the study in the report.
18 | 6 | No | None
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
19 | 1 | This is a very clear and excellently written review. I have only two possible suggestions: 1) given the consistent evidence on higher specificity of CCTA-HF, and consistent findings from low quality studies, it seems one could state that it is likely that for patients undergoing CCTA, use of HF would modestly reduce the number referred for ICA. One could use the current VA data to calculate that impact. Given that only 20% are referred to ICA after CCTA, that number would likely be small. | We calculated the estimated number of ICAs prevented per 1000 ICAs in the previous ESP report. We have added a few sentences to the “Considerations for the Use of HeartFlow in VA” section on the findings from the calculation from the previous report.
20 | 1 | 2) I would more explicitly state the distinct types of research needed. Once could easily do a study of patients undergoing CCTA and randomize them to HF or not and measure change in ICA. More important given new recommendations would be to assess CT with HF as an alternative to other non-invasive strategies for moderate risk patients. | We have added a description of the specific types of research needed - controlled trials comparing CCTA alone to HeartFlow and HeartFlow to other noninvasive strategies to the executive summary and the future research section.
21 | 2 | The clinical question addressed by the 2019 review was important and remains so. The earlier review was excellent and this update is a useful adjunct. I found no shortcomings in the methodology. It would probably be useful for general readers, to have a bit more description about how the technology functions and what is entailed. | We have added a bit more detail to the description of the HeartFlow technology. Readers are also referred to our earlier report for more detail.
22 | 2 | In thinking about whether this technology could be adopted by VA it would be nice to have some information about relative cost. | We agree that information on relative cost could be useful, but we do not have ready access to this data and analysis of VA costs data was outside the scope of this report.
23 | 4 | Page 21, line 4: The conclusion that “most patients receiving CCTA have normal or non-obstructive results and do not end up requiring ICA” is undoubtedly at least partially true, however a second viable explanation would be that the exam shows extensive coronary artery disease not amenable to ICA intervention. In my experience, this is not uncommon in the VA population, and is probably an equally valuable result by obviating the need for the patient to undergo an invasive procedure without significant therapeutic value. As I see it, one of the major roles of CCTA (with or without CT-FFR) should be to act as a gatekeeper to the cath lab, so that only those who will truly benefit will need an invasive (and relatively expensive) procedure. | We agree and have added that extensive coronary disease may also account for those not going on to ICA.
24 | 4 | Page 21, line 16: correct term should be “CT technologist”, not technician. | Corrected.
25 | 4 | Page 25, line 44: correct title: Acting Director, VHA National Radiology Program | Corrected.

### REFERENCES

1 Celeng C, Leiner T, Maurovich-Horvat P, . Anatomical and functional computed tomography for diagnosing hemodynamically significant coronary artery disease: A meta-analysis. JACC: Cardiovascular Imaging. 2018:S1936–1878X(1918)30681–30688.
2 Hamon M, Geindreau D, Guittet L, Bauters C, Hamon M. Additional diagnostic value of new ct imaging techniques for the functional assessment of coronary artery disease: A meta-analysis. European Radiology. 2019;29(6):3044–3061.30617482
3 Pontone G, Guaricci AI, Palmer SC, . Diagnostic performance of non-invasive imaging for stable coronary artery disease: A meta-analysis. Int J Cardiol. 2020;300:276–281.31748186
4 Driessen RS, Danad I, Stuijfzand WJ, . Comparison of coronary computed tomography angiography, fractional flow reserve, and perfusion imaging for ischemia diagnosis. Journal of the American College of Cardiology. 2019;73(2):161–173.30654888
5 Pontone G, Baggiano A, Andreini D, . Stress computed tomography perfusion versus fractional flow reserve ct derived in suspected coronary artery disease: The PERFECTION study. JACC: Cardiovascular Imaging. 2019;12(8 Pt 1):1487–1497.30343073
6 Pontone G, Baggiano A, Andreini D, . Dynamic stress computed tomography perfusion with a whole-heart coverage scanner in addition to coronary computed tomography angiography and fractional flow reserve computed tomography derived. JACC: Cardiovascular Imaging. 2019;12(12):2460–2471.31005531
7 Bom MJ, Driessen RS, Kurata A, . Diagnostic value of comprehensive on-site and off-site coronary ct angiography for identifying hemodynamically obstructive coronary artery disease. Journal of Cardiovascular Computed Tomography. 2021;15(1):37–45.32540206
8 Cami E, Tagami T, Raff G, . Importance of measurement site on assessment of lesion-specific ischemia and diagnostic performance by coronary computed tomography angiography-derived fractional flow reserve. Journal of Cardiovascular Computed Tomography. 2020;29:29.
9 Ko BS, Linde JJ, Ihdayhid AR, . Non-invasive ct-derived fractional flow reserve and static rest and stress ct myocardial perfusion imaging for detection of haemodynamically significant coronary stenosis. The International Journal of Cardiovascular Imaging. 2019;35(11):2103–2112.31273632
10 Tanigaki T, Emori H, Kawase Y, . Qfr versus FFR derived from computed tomography for functional assessment of coronary artery stenosis. JACC: Cardiovascular Interventions. 2019;12(20):2050–2059.31648766
11 Anastasius M, Maggiore P, Huang A, . The clinical utility of FFR<sub>ct</sub> stratified by age. Journal of Cardiovascular Computed Tomography. 2020;23:23.
12 Fairbairn TA, Dobson R, Hurwitz-Koweek L, . Sex differences in coronary computed tomography angiography-derived fractional flow reserve: Lessons from advance. Jacc: Cardiovascular Imaging. 2020;13(12):2576–2587.32861656
13 Patel MR, Norgaard BL, Fairbairn TA, . 1-year impact on medical practice and clinical outcomes of FFR<sub>ct</sub>: The advance registry. JACC: Cardiovascular Imaging. 2020;13(1 Pt 1):97–105.31005540
14 Fairbairn TA, Nieman K, Akasaka T, . Real-world clinical utility and impact on clinical decision-making of coronary computed tomography angiography-derived fractional flow reserve: Lessons from the advance registry. European Heart Journal. 2018;39(41):3701–3711.30165613
15 Nous F, Budde RPJ, Fairbairn TA, . Temporal changes in FFR<sub>ct</sub>-guided management of coronary artery disease - lessons from the advance registry. Journal of Cardiovascular Computed Tomography. 2021;15(1):48–55.32418861
16 Pontone G, Weir-McCall JR, Baggiano A, . Determinants of rejection rate for coronary ct angiography fractional flow reserve analysis. Radiology. 2019;292(3):597–605.31335283
17 Shiono Y, Matsuo H, Kawasaki T, . Clinical impact of coronary computed tomography angiography-derived fractional flow reserve on japanese population in the advance registry. Circulation Journal. 2019;83(6):1293–1301.30996150
18 Colleran R, Douglas PS, Hadamitzky M, . An FFRCT diagnostic strategy versus usual care in patients with suspected coronary artery disease planned for invasive coronary angiography at german sites: One-year results of a subgroup analysis of the platform (prospective longitudinal trial of FFRCT: Outcome and resource impacts) study. Open Heart. 2017;4(1).
19 Douglas PS, Pontone G, Hlatky MA, . Clinical outcomes of fractional flow reserve by computed tomographic angiography-guided diagnostic strategies vs Usual care in patients with suspected coronary artery disease: The prospective longitudinal trial of FFR(ct): Outcome and resource impacts study. European Heart Journal. 2015;36(47):3359–3367.26330417
20 Douglas PS, De Bruyne B, Pontone G, . 1-year outcomes of FFRCT-guided care in patients with suspected coronary disease: The platform study. Journal of the American College of Cardiology. 2016;68(5):435–445.27470449
21 Hlatky MA, De Bruyne B, Pontone G, . Quality-of-life and economic outcomes of assessing fractional flow reserve with computed tomography angiography: Platform. Journal of the American College of Cardiology. 2015;66(21):2315–2323.26475205
22 Andreini D, Modolo R, Katagiri Y, . Impact of fractional flow reserve derived from coronary computed tomography angiography on heart team treatment decision-making in patients with multivessel coronary artery disease: Insights from the syntax iii revolution trial. Circulation: Cardiovascular Interventions. 2019;12(12):e007607.31833413
23 Baggiano A, Fusini L, Del Torto A, . Sequential strategy including FFR<sub>ct</sub> plus stress-ctp impacts on management of patients with stable chest pain: The stress-ctp ripcord study. Journal of Clinical Medicine. 2020;9(7):08.
24 Curzen NP, Nolan J, Zaman AG, Norgaard BL, Rajani R. Does the routine availability of ct-derived FFR influence management of patients with stable chest pain compared to ct angiography alone?: The FFRCT ripcord study. JACC Cardiovascular Imaging. 2016;9(10):1188–1194.27568119
25 Fares A, Alaiti MA, Alkhalil A, . Real world utilization of computed tomography derived fractional flow reserve: Single center experience in the united states. Cardiovascular Revascularization Medicine. 2019;20(12):1043–1047.30833210
26 Ihdayhid AR, Norgaard BL, Gaur S, . Prognostic value and risk continuum of noninvasive fractional flow reserve derived from coronary ct angiography. Radiology. 2019;292(2):343–351.31184558
27 Jang J, Krishnaswami A, Rogers C, Hung Y, Sengupta S. The impact of fractional flow reserve derived from coronary computed tomography angiography in a managed healthcare system – kaiser permanente northern california [abstract #50]. Journal of Cardiovascular Computed Tomography. 2016;10(3):S1–S96.
28 Jensen JM, Bøtker HE, Mathiassen ON, . Computed tomography derived fractional flow reserve testing in stable patients with typical angina pectoris: Influence on downstream rate of invasive coronary angiography. European Heart Journal Cardiovascular Imaging. 2018;19(4):405–414.28444153
29 Norgaard BL, Mortensen MB, Parner E, . Clinical outcomes following real-world computed tomography angiography-derived fractional flow reserve testing in chronic coronary syndrome patients with calcification. European heart journal cardiovascular Imaging. 2020;13:13.
30 Norgaard BL, Hjort J, Gaur S, . Clinical use of coronary cta-derived FFR for decision-making in stable cad. JACC: Cardiovascular Imaging. 2017;10(5):541–550.27085447
31 Norgaard BL, Gormsen LC, Botker HE, . Myocardial perfusion imaging versus computed tomography angiography-derived fractional flow reserve testing in stable patients with intermediate-range coronary lesions: Influence on downstream diagnostic workflows and invasive angiography findings. Journal of the American Heart Association. 2017;6(8):22.
32 Rabbat M, Leipsic J, Bax J, . Fractional flow reserve derived from coronary computed tomography angiography safely defers invasive coronary angiography in patients with stable coronary artery disease. Journal of Clinical Medicine. 2020;9(2):24.
33 Van Belle E, Raposo L, Bravo Baptista S, . Impact of an interactive ct/FFR<sub>ct</sub> interventional planner on coronary artery disease management decision making. JACC: Cardiovascular Imaging. 2021;04:04.