# WHAT IS THE RELATIONSHIP BETWEEN TIMING OF INTRODUCTION OF COMPLEMENTARY FOODS/BEVERAGES AND MICRONUTRIENT STATUS?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between timing of introduction of complementary foods and beverages and micronutrient status?

### What is the answer to the question?

- Moderate evidence suggests that introducing complementary foods and beverages at 4 months of age compared to 6 months of age offers no long term advantages or disadvantages in terms of iron status among healthy, full-term infants who are breastfed, fed iron fortified formula, or both.
- There is not enough evidence to determine the relationship between timing of introduction of complementary foods and beverages and zinc, vitamin D, vitamin B12, folate, or fatty acid status.

### Why was this question asked?

- This important public health question was identified and prioritized as part of the U.S. Department of Agriculture and Department of Health and Human Services Pregnancy and Birth to 24 Months Project.

### How was this question answered?

- A team of Nutrition Evidence Systematic Review staff conducted a systematic review in collaboration with a group of experts called a Technical Expert Collaborative

### What is the population of interest?

- Generally healthy infants and toddlers who were fed complementary foods and beverages from ages 0-24 months and had micronutrient status examined through 24 months of age

### What evidence was found?

- This review includes 9 studies.
- These studies compared the age when complementary foods and beverages were first introduced and micronutrient status.
- Complementary foods and beverages are foods and beverages other than human milk or infant formula provided to an infant or young child.
- Most studies found no relationship the age when complementary feeding started and micronutrient status.
- Studies need to consider other factors that could impact this relationship.

### How up-to-date is this review?

- This review includes literature from 1/1980 to 3/2016.

## FULL REVIEW

### Systematic review question

What is the relationship between timing of introduction of complementary foods and beverages and micronutrient status?

### Conclusion statement

Moderate evidence suggests that introducing complementary foods and beverages at 4 months of age compared to 6 months of age offers no long term advantages or disadvantages in terms of iron status among healthy, full-term infants who are breastfed, fed iron fortified formula, or both.

There is not enough evidence to determine the relationship between timing of introduction of complementary foods and beverages and zinc, vitamin D, vitamin B12, folate, or fatty acid status.

### Grade

Moderate: Iron Status; Grade Not Assignable: Zinc, Vitamin D, Vitamin B12, Folate, and Fatty Acid Status

### Summary

- Complementary foods and beverages (CFB) were defined as foods and/or beverages other than human milk or infant formula (liquids, semisolids, and solids) provided to an infant or young child to provide nutrients and energy. This systematic review includes studies that compared different ages at which complementary foods were introduced.
- Micronutrient status outcomes included iron, zinc, vitamin D, vitamin B12, folate, and/or fatty acid status from birth to 24 months of age.
- Nine studies published from 1/1980 to 3/2016 met the inclusion criteria for this systematic review, with most studies examining the relationship between timing of introduction of CFB and iron status. Few studies examined zinc, vitamin D, vitamin B12, folate, and/or fatty acid status.
- The majority of studies reported no significant associations between timing of CFB introduction and micronutrient status.
- Additional factors that need to be considered in examining the relationship between the age at which CFB are introduced and micronutrient status include: birth weight, post-natal growth, type of feeding (breast, formula, or mixed feedings), iron stores at birth, and intake and absorption of iron from sources other than human milk, including types and amounts of CFB being consumed.

### Description of the evidence

Nine articles were included in the systematic review that examined the relationship between the timing of first introduction of CFB and micronutrient status from birth to 24mo of age. Most of the studies examined the relationship between timing of introduction of CFB and iron status [1–7], with 2 studies assessing the relationship with zinc [3, 4], and 1 study each examining folate [8], vitamin B12 [8], and vitamin D status [9]. There were no studies identified that assessed fatty acid status in relation to the timing of CFB introduction (Table 1).

The studies included subjects who were healthy, with many excluding subjects with illnesses or conditions that could impact complementary feeding or nutritional status. In addition, the studies included subjects who had a normal birthweight (≥2500g) and/or were born at full term (>37 weeks (wk)), though a few did not describe the birth weight or gestational age of subjects [1, 4, 6]. Per the inclusion criteria, the studies were conducted in countries that were ranked as very high or high on the Human Development Index [10]. Two studies specified that the sample was majority white [3, 9], and 1 included a population that consisted of 50% white and 50% Asian children [5]. The other studies did not specify the racial/ethnic background of subjects; but they were conducted in representative populations from the countries in which they were conducted (i.e., China, Greece, Iceland, Iran, the UK, and Norway).

#### Timing of CFB Introduction and Iron Status

Seven studies examined the relationship between timing of introduction of CFB and iron status, including 3 RCTs [2–4], 1 prospective cohort study [7], 1 nested case-control study [5], and 2 case-control studies [1, 6] (Table 1).

All 3 RCTs examined the effects of introducing CFB at different ages on iron status. Jonsdottir et al. [2] randomized exclusively BF infants to start receiving CFB at either 4mo or 6mo of age. Kattelmann et al. [3] randomized FF infants to receive CFB beginning at either 3-4mo or 6mo of age. Details regarding the infant formula consumed, and whether it was fortified with iron or zinc, were not provided, as subjects consumed commercial infant formulas of the parents’ choice. However, based on the time during which the study was conducted in the US, it can be assumed that those formulas were supplemented with iron (~10-12 mg/L, though “low iron” formulas (1.1-1.5 mg/L) [11] were also available). Lonnerdal et al. [4] randomized FF infants to receive CFB at 4mo, or to continue exclusive FF until 7mo. The formula consumed by infants contained 7mg/L iron and 7mg/L zinc; the micronutrient content of the cereal provided to infants at 4mo was not described. Jonsdottir et al. [2] and Kattelmann et al. [3] did not provide CFB to subjects, nor were subjects provided with specific instructions as to the types of CFB to introduce; so CFB were either commercial or home-prepared foods selected by the parents. Jonsdottir et al. [2] reported that among infants who received CFB, mean daily intake of iron was only 0.6 mg, with the main dietary sources of iron being infant cereals (67%), infant formula (17%), and fruit purées (8%). In addition, they reported that iron intake did not correlate with any iron status indices at 6mo, nor did total food or formula intake. Kattelmann et al. [3] reported that while the infants who received CFB earlier had significantly greater iron intake at 4, 5, and 6mo, mean iron intakes in both groups were reportedly adequate, and there were no differences in mean iron intake between groups after 6mo of age. Further, Kattelmann et al. [3] also reported that there were no differences between the groups in meat intake (red meat, poultry, or seafood) at 12mo or 24mo of age.

The observational studies defined the timing of introduction of CFB in different ways, and included subjects with varied infant milk feeding practices (i.e., whether they were primary fed breast milk, infant formula, and/or cow’s milk at the time when complementary feeding began). Ghorashi et al. [1] and Morton et al. [5] both analyzed age of introduction to CFB as a continuous variable, which represented the mean, in months, when solid food was first introduced. Subjects in Ghorashi et al. [1] were majority BF (65%), though 11% were FF, and 25% received a mixture of breast milk, infant formula, and cow’s milk, and there were no differences in milk feeding practices between cases of iron deficiency and controls. Approximately 25% of subjects in Morton et al. [5] were BF, and a significantly greater percentage of iron deficient compared to iron sufficient infants were fed full cow’s milk before 6mo of age (44% vs. 7%). Thorsdottir et al. [7] examined the duration of exclusive breastfeeding as a continuous variable, which was based on monthly assessments of whether infants were exclusively BF or had been introduced to other types of liquids or solids besides breast milk. While this definition could include infant formula, the authors noted that in Iceland, where the study was conducted, it is commonly recommended that infants weaned from breast milk should receive cow’s milk after the age of 6mo. Tympa-Psirropoulou et al. [6] looked at age of introduction to CFB and age of introduction to meat. While age of CFB introduction was not defined, age of meat introduction was examined categorically, comparing introduction at 5, 6, and 7mo of age. Iron deficient cases in this study had shorter duration of breastfeeding, and were more likely to be fed fresh cow’s milk vs. fortified cow’s milk, after BF or infant formula were discontinued, compared to iron sufficient control subjects.

Several different markers of iron status were assessed at a variety of ages from 4mo through 24mo in the studies included in this systematic review, including hemoglobin (Hb), serum ferritin (SF), mean corpuscular volume (MCV), hematocrit (Hct), red cell distribution width (RDW), total iron binding capacity (TIBC), transferrin receptor (TfR), and zinc-protoporphyrin (ZPP). Reference values for markers of iron status in infants and toddlers up to 24mo of age are not well developed, and suggestions have been made to reevaluate the criteria for evaluating iron status in young children [12]. A discussion of results for each marker reported in the studies in this systematic review is found below.

##### Results for Hemoglobin (Hb), Iron Deficiency (ID), Iron Deficiency Anemia (IDA), and Anemia

All 7 studies that examined iron status assessed Hb as a marker of ID in relation to the timing of CFB introduction, though few significant findings were reported. The studies varied in terms of the age at which Hb was measured and how ID, IDA, and anemia were defined, as well as in regards to the populations examined.

None of the RCTs including BF and FF infants in this systematic review reported any significant differences in mean Hb between infants introduced to CFB at 4mo vs. 6 or 7mo [2–4]. In addition, Kattelmann et al. [3] found no significant differences in the proportion with low Hb (<100g/L), and Jonsdottir et al. [2] found no significant differences in the proportion of infants with IDA (defined as Hb<105g/L, MCV<74f, and SF<12ug/L) or ID (defined as MCV<74fl and SF<12ug/L).

None of the observational studies of BF, FF and mixed-fed infants reported significant associations between age of CFB introduction and Hb. Ghorashi et al. [1] found no significant differences in age of CFB introduction between cases with IDA (Hb<10.5g/dl) and controls, nor did Morton et al. [5] between IDA cases (Hb<11g/dl and SF<10ug/L) and iron sufficient controls, or Tympa-Psirropoulou et al. [6] between IDA cases (Hb<11g/dl, SF<10ug/l, and other low red-cell indices) and controls. Thorsdottir et al. [7] found no significant associations between duration of exclusive BF and Hb at 12mo or prevalence of IDA (defined as Hb<105g/l, SF<12ug/l, and MCV<74fl). However, Tympa-Psirropoulou et al. [6] did find that a significantly higher percentage of controls were introduced to meat earlier (at 5mo and 6mo), and a significantly higher percentage of IDA cases were introduced to meat later (at 7mo).

##### Results for Serum Ferritin (SF)

Three studies examined SF in relation to the timing of CFB introduction, including 2 of the RCTs and 1 prospective cohort study. Jonsdottir et al. [2] reported that exclusively breastfed infants introduced to CFB at 4mo had significantly higher median serum ferritin at 6mo compared to those who were still exclusively BF at 6 mo. There were no significant differences between groups in the proportion of infants with SF<12ug/L. Kattelmann et al. [3] found no significant differences in mean SF at 12 or 24mo of age between FF infants introduced to CFB at 4mo vs. 6mo, or in the proportion with low SF (<12ug/L). Thorsdottir et al. [7] found that longer duration of exclusive BF (i.e., later introduction of CFB) was associated with significantly higher SF at 12mo.

##### Results for Other Measures of Iron Status

A number of other measures or indicators of iron status were also examined. Three studies, including 2 RCTs and 1 cohort study, assessed MCV in relation to the timing of CFB introduction, all reporting no significant associations. Jonsdottir et al. [2] found no significant differences in MCV at 6mo, and Kattelmann et al. [3] found no significant differences in MCV at 12 or 24mo of age between infants introduced to CFB at 4mo vs. 6mo. In addition, Thorsdottir et al. [7] found that longer duration of exclusive BF was not significantly associated with MCV at 12mo. At 6 mo Jonsdottir et al. [2] found no significant differences in RDW or TIBC between infants introduced to CFB at 4mo compared to those who were exclusively BF until 6 mo. Finally, Thorsdottir et al. [7] found no significant associations between duration of exclusive BF and TfR at 12mo of age.

#### Timing of CFB Introduction and Zinc Status

Two RCTs examined the relationship between timing of CFB introduction and zinc status (Table 2). Kattelmann et al. [3], as described above, randomized FF infants to receive CFB (commercial or home-prepared foods selected by the parents) beginning at 3-4mo or 6mo of age. Details regarding the infant formula (selected by parents) consumed were not provided however, based on the time during which the study was conducted, it can be assumed that those formulas were fortified with zinc. Lonnerdal et al. [4] randomized FF infants to receive CFB (cereal) at 4mo, or to continue exclusive FF until 7mo. The nutritional content of the cereal was not described but the formula consumed by all infants contained 7mg/L iron and 7mg/L zinc.

Results from Kattelmann et al. [3] showed no differences in serum zinc levels at 12 or 24mo of age between study groups. Lonnerdal et al. [4] reported that earlier introduction of CFB at 4mo vs. 7mo resulted in significantly higher levels of plasma zinc at 6mo and 7mo of age.

#### Timing of CFB Introduction and Folate and Vitamin B12 Status

One prospective cohort study was identified that examined the relationship between timing of CFB introduction and folate and vitamin B12 status in BF infants (Table 2). In this study, Hay et al. [8] defined CFB as foods and beverages other than breast milk or breast milk substitutes, and analyzed timing continuously as the time (in days) since the introduction of CFB. Results showed that in BF infants, timing of CFB introduction was not significantly associated with serum cobalamin at 6 or 12mo of age. However, earlier introduction of CFB was associated with decreased serum folate at 6mo, but not 12mo.

#### Timing of CFB Introduction and Vitamin D Status

One RCT was identified that examined the relationship between timing of CFB introduction and vitamin D status (Table 2). In this study, Bainbridge et al. [9] randomly assigned FF infants to receive rice cereal, in addition to formula, from 16 to 26wk, or to continue exclusive FF through 26wk. All infants consumed the same amount of vitamin D- and iron-fortified formula. Use of supplemental vitamin D among infants or their mothers was not described. Results showed no significant differences between groups in serum 25 hyroxyvitamin D at 26wk, or change between 16 and 26wk.

### Evidence synthesis

Moderate evidence suggests that introducing CFB at 4mo compared to 6mo of age offers no long term advantages or disadvantages in terms of iron status among healthy, full-term infants who are BF, fed iron fortified formula, or both. There is not enough evidence to determine the relationship between timing of introduction of CFB and zinc, vitamin D, vitamin B12, folate, or fatty acid status.

The RCTs included in this systematic review were designed to directly examine the effects of the specific timing of introduction of CFB for the first time on micronutrient status, while the observational studies examined the direction and strength of the association between timing of introduction and micronutrient status. The definitions and analytic techniques used in the observational studies were inconsistent, making it difficult to determine the specific ages at which CFB were introduced, particularly when duration of exclusive BF was analyzed as a continuous variable. Therefore, the data from these studies were not relied upon as heavily in drawing conclusions about timing of CFB introduction and its impact on micronutrient status.

The reported effects from the RCTs, which had fewer concerns related to internal validity, were also more likely to be the true effects of the timing of introduction of CFB and micronutrient status compared to the results from the prospective cohort studies. In particular, the major methodological limitation of concern from the latter studies relates to confounding bias from factors such as education, socioeconomic status, sex, maternal age, race/ethnicity, feeding practices aside from CFB (breast milk vs. infant formula), birth size, and gestational age. Few of the cohort studies described baseline characteristics of subjects, making it impossible to determine whether the comparison groups differed on any of these potential confounders at baseline. In addition, the observational studies adjusted for few of the key confounders listed above in outcome analyses. Finally, it is likely that several studies were not powered or did not include sufficient sample size to adequately analyze results from certain sub-sets of study subjects.

Most of the studies included subject populations that were generalizable to the US population, though there is a lack of data that applies to lower-income or racial/ethnic minority populations. While the interventions/exposures and nutritional status biomarkers considered in the studies are applicable to the US population, most of the studies examined subjects who were not at risk for insufficient iron stores, and therefore, the clinical or practical significance of the findings for deficient subjects is difficult to determine. Furthermore, because few of the studies reported the types and amounts of CFB consumed by infants, it is also difficult to determine whether the types of CFB introduced to infants were similar to those commonly fed to US infants.

### Research recommendations

In order to better assess the relationship between the timing of introduction of CFB and micronutrient status, additional research is needed:

- Additional studies, including both randomized controlled trials and prospective cohort studies with sufficient sample sizes, that examine the specific age at which CFB are introduced and nutritional status outcomes of public health concern, primarily iron status, but also zinc, vitamin D, vitamin B12, folate, and/or fatty acid status.
- Research that adjusts for key confounding factors, such as education, socioeconomic status, sex, maternal age, race/ethnicity, feeding practices aside from CFB (breast milk vs. infant formula), birth size, and gestational age.
- Research in more diverse populations with varying racial/ethnic and socioeconomic backgrounds, and with increased risk of poor nutritional status (including ID, and IDA).
- Research regarding the timing of introduction to CFB in relation to micronutrient status should eventually incorporate cut-points of biomarkers that are based on reference data in infants ages 0-12mo, for which development is in progress.

Table 1 Description of studies examining the relationship between timing of first introduction of any complementary foods and beverages (CFB) and iron status

Reference; study design; n; country | Intervention or exposure | Results for hemoglobin (Hb) | Results for serum ferritin (SF) | Results for other iron status measures
Randomized Controlled Trials
Jonsdottir, 2012 (2); 100; Iceland | Exclusively BF infants randomized to receive CFB: 4mo vs. 6mo | Hb, IDA, ID at 6mo: No significant group differences | SF at 6mo: 70.0 ug/L (IQR=73.3) vs. 44.0 ug/L (IQR=53.8); P=0.02; SF<12ug/L at 6mo: v | RDW, TIBC at 6mo: No significant group differences
Kattelmann, 2001 (3); 133; US | FF infants randomized to receive CFB: 3-4mo vs. 6mo of age | Hb, Hb>100g/L at 12 or 24mo: No significant group differences | SF, SF<12ug/L at 12 or 24mo: No significant group differences | MCV, MCV<70um at 12 or 24mo: No significant group differences
Lonnerdal, 1990 (4); NR; China | FF infants randomized to receive CFB: 4mo vs. 7mo of age | Hb at 5, 6, or 7mo: No significant group differences
Observational Studies
Ghorashi, 2008 (1); Case-Control Study; 60 IDA Cases, 60 Controls; Iran | Age of CFB introduction: Mean, mo | IDA cases (Hb<10.5g/dl) vs. controls: No significant group differences
Morton, 1988 (5); Nested Case-Control Study; 55; UK | Age of CFB introduction: Mean, mo | IDA cases (Hb<11g/dL, SF<10ug/L) vs. controls at 6mo: No significant group differences
Thorsdottir, 2003 (7); Prospective Cohort Study; 114; Iceland | Age of CFB introduction: Duration of exclusive BF; continuous | Hb or IDA at 12mo: No significant associations | SF at 12mo: r^2^=0.05; P=0.011 | MCV, TfR at 12mo: : No significant associations
Tympa-Psirropoulou, 2005 (6); Case-Control Study; 75 IDA Cases, 75 Controls; Greece | Age of CFB introduction: Not defined | IDA cases (Hb<11g/dl) vs. controls: No significant group differences
Tympa-Psirropoulou, 2005 (6); Case-Control Study; 75 IDA Cases, 75 Controls; Greece | Age of meat introduction: Percentage introduced at 5mo, 6mo, 7mo | IDA cases vs. controls: 5.3% vs.10.7%, 45.3% vs. 81.3%, 8% vs. 49.3%; P<0.001

Table 2 Description of studies examined the relationship between timing of introduction of complementary foods and beverages (CFB) and zinc, vitamin B12, folate, and vitamin D status

Reference; study design; n; country | Intervention or exposure | Results
Zinc status
Kattelmann, 2001 (3); RCT; 133; US | FF infants randomized to receive CFB: 3-4mo vs. 6mo of age | Serum zinc at 12 and 24mo: No significant group differences
Lonnerdal, 1990 (4); NR; China | FF infants randomized to receive CFB: 4mo vs. 7mo of age | Plasma zinc at 6mo: 0.85±0.13 vs. 0.78±0.15, P<0.05; Plasma zinc at 7mo: 0.87±0.18 vs. 0.75±0.15, P<0.05
Folate and vitamin B12 status
Hay, 2008 (8); Prospective Cohort Study; 241; Norway | Age of CFB introduction: Time in d since CFB introduction (end of exclusive BF) | Serum folate at 6mo: −0.26; P<0.001; Serum folate at 12 mo: No significant associations; Serum cobalamin at 6 or 12mo: No significant associations
Vitamin D status
Bainbridge, 1996 (9); RCT; 41; US | FF infants randomized to receive CFB: 16wk vs. 26wk of age | 25-hyroxyvitamin D or 1, 25-dihydroxyvitamin D at 26wk, or change from 16 to 26wk: No significant group differences

### Included articles

1 Ghorashi, ., Supplemental food may not prevent iron-deficiency anemia in infants. Indian J Pediatr, 2008. 75(11): p. 1121–4.18810337
2 Jonsdottir, ., Timing of the introduction of complementary foods in infancy: a randomized controlled trial. Pediatrics, 2012. 130(6): p. 1038–45.23147979
3 Kattelmann, ., Effect of timing of introduction of complementary foods on iron and zinc status of formula fed infants at 12, 24, and 36 months of age. J Am Diet Assoc, 2001. 101(4): p. 443–7.11320951
4 Lonnerdal, ., Effects of formula protein level and ratio on infant growth, plasma amino acids and serum trace elements. II. Follow-up formula. Acta Paediatr Scand, 1990. 79(3): p. 266–73.2333740
5 Morton, ., Iron status in the first year of life. J Pediatr Gastroenterol Nutr, 1988. 7(5): p. 707–12.3183875
6 Tympa, P., ., Nutritional risk factors for iron-deficiency anaemia in children 12-24 months old in the area of Thessalia in Greece. Int J Food Sci Nutr, 2005. 56(1): p. 1–12.16019310
7 Thorsdottir, I., ., Iron status at 12 months of age -- effects of body size, growth and diet in a population with high birth weight. Eur J Clin Nutr, 2003. 57(4): p. 505–13.12700611
8 Hay, ., Folate and cobalamin status in relation to breastfeeding and weaning in healthy infants. Am J Clin Nutr, 2008. 88(1): p. 105–14.18614730
9 Bainbridge, R.R., ., Effect of rice cereal feedings on bone mineralization and calcium homeostasis in cow milk formula fed infants. J Am Coll Nutr, 1996. 15: p. 383–8.8829094

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. This is the analytic framework for the systematic review conducted to examine the relationship between timing of introduction of complementary foods and beverages and micronutrient status.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts all contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on the timing of introduction of CFB and micronutrient status. For this systematic review, the target population considered was generally healthy infants fed humna milk, infant formula, or both, who had micronutrient status measured through age 24 months. The interventions or exposures considered was the timing of introduction of CFB and their comparators were different time of introduction of CFB. Complementary feeding is defined as the process that starts when human milk or infant formula is complemented by other foods and beverages. The complementary feeding period typically continues to 24 months as the young child transitions fully to family foods.Complementary foods and beverages (CFB) are foods and beverages (liquids, semisolids, and solids) other than human milk or infant formula, provided to an infant or young child to provide nutrients and energy. The outcomes considered were iron, zinc, vitamin D, vitamin B12, folate, and/or fatty acid status. The key confounders were education, socioeconomic status, sex, maternal age, race and/or ethnicity, milk feeding practices (breast milk, infant formula, or both), birth size, and gestational age.

## SEARCH PLAN AND RESULTS

### Inclusion and exclusion criteria

The inclusion and exclusion criteria are a set of characteristics to determine which studies will be included or excluded in the systematic review. This table provides the inclusion and exclusion criteria for the systematic review question: What is the relationship between timing of introduction of complementary foods and beverages and micronutrient status?

Table 3 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | Randomized controlled trials | Cross-sectional studies
Study design | Non-randomized controlled trials | Uncontrolled studies
Study design | Prospective cohort studies | Pre/post studies without a control
Study design | Retrospective cohort studies | Narrative reviews
Study design | Case-control studies | Systematic reviews
Study design | Pre/post studies with a control | Meta-analyses
Independent variable (intervention or exposure) | Timing of introduction to complementary foods and beverages (i.e., foods and beverages other than human milk or infant formula (liquids, semisolids, and solids) provided to an infant or young child to provide nutrients and energy) | Consumption of fluid cow’s milk before 12 months of age
Comparator | Different timing of introduction of CFB | N/A
Dependent variables (outcomes) | Iron status, including incidence of iron deficiency and anemia | N/A
| Zinc status
| Vitamin D status
| Vitamin B12 status
| Folate status
| Fatty acid status
Date range | January 1980 - March 2016
Language | Studies published in English | Studies published in languages other than English
Publication status | Studies published in peer-reviewed journals | Grey literature, including unpublished data, manuscripts, reports, abstracts, conference proceedings
Country^1,^ ^2,^ ^3^ | Studies conducted in Very High or High Human Development Countries | Studies conducted in Medium or Low Human Development Countries
Study participants | Human subjects | Hospitalized patients, not including birth and immediate post-partum hospitalization of healthy babies
Study participants | Males
Study participants | Females
Age of study participants | Age at intervention or exposure: Infants (0-12mo); Toddlers (12-24mo) | Age at intervention or exposure: Child (2-5 years (y)); Child (6-12y); Adolescents (13-18y); Adults (19y and older); Older adults (65 to 79y); Older adults (80+y)
Age of study participants | Age at outcome: Infants (0-12mo); Toddlers (12-24mo) | Age at outcome: Child (2-5y); Child (6-12y); Adolescents (13-18y); Adults (19y and older); Older adults (65 to 79y); Older adults (80+y)
Health status of study participants | Studies done in generally healthy populations | Studies that exclusively enroll subjects with a disease or with the health outcome of interest
Health status of study participants | Studies done in populations where infants were full term (≥37wk gestational age) | Studies done in hospitalized or malnourished subjects
Health status of study participants | Studies done in populations with elevated chronic disease risk, or that enroll some participants with a disease or with the health outcome of interest | Studies of exclusively pre-term babies (gestational age <37wk) or babies that are small for gestational age (<2500g)
Health status of study participants | | Studies of subjects with infectious diseases (e.g. HIV/AIDS) (or with mothers diagnosed with an infectious disease)

1 United Nations Development Programme. Human Development Report 2014: Reducing Vulnerabilities and Building Resilience. Available from: http://hdr.undp.org/en/content/human-development-report-2014. (19)

2 Medium Development countries were originally included, but due to concerns about generalizability to the U.S. of study participants (i.e., baseline health status) and complementary foods and beverages typically consumed, a decision was made to exclude “Medium” countries in October 2017.

3 When a country was not included in the HDI ranking, country classification from the World Bank was used instead (51)

### Search terms and electronic databases used

#### PubMed, US National Library of Medicine (https://www.nlm.nih.gov/bsd/medline.html) (1966 to 9 March 2016)

Date(s) Searched 12/9/2015; 3/9/2016

Search Terms:

((Complementary OR supplementary OR wean* OR transition* OR introduc* OR “Infant Nutritional Physiological Phenomena”[Mesh:noexp] OR weaning[mesh])

AND (feeding* OR food* OR beverage*[tiab] OR beverages[mh] OR eating OR diet[tiab] OR diet[mh] OR meal*[tiab] OR meals[mh] OR “Food and Beverages”[Mesh] OR diets[tiab] OR cereal*[tiab] OR “Edible Grain”[Mesh] OR bread*[tiab] OR whole grain* OR juice*[tiab] OR milk[tiab] OR “Milk”[Mesh] OR dairy[tiab] OR “Dairy Products”[Mesh] OR meat[tiab] OR cheese[tiab] OR yogurt[tiab] OR yoghurt*[tiab] OR fruit*[tiab] OR “Fruit”[Mesh] OR vegetable*[tiab] OR “Vegetables”[Mesh] OR egg*[tiab] OR “Eggs”[Mesh] OR nut[tiab] OR nuts[tiab] OR peas[tiab] OR beans[tiab] OR legume*[tiab] OR snack*[tiab])) OR “infant food”[mesh]

AND

nutritional status[mh] OR nutritional status*[tiab] OR Nutrition Status*[tiab] OR “Nutritional Requirements”[Mesh] OR Iron[mh] OR iron[tiab] OR “Anemia”[Mesh] OR “Anemia”[tiab] OR iron deficien*[tiab] OR ferritin*[tiab] OR ferrous[tiab] OR “Transferrin”[Mesh] OR “Transferrin”[tiab] OR zinc OR “Vitamin D”[Mesh] OR “Vitamin D”[tiab] OR “Vitamin D Deficiency”[Mesh] OR “Vitamin B 12”[Mesh] OR “Vitamin B 12”[tiab] OR “Vitamin B12”[tiab] OR “Vitamin B 12 Deficiency”[Mesh] OR Cobamide*[tiab] OR Cobalamin*[tiab] OR Cyanocobalamin[tiab] OR Folate[tiab] OR “Folic Acid”[Mesh] OR folacin[tiab] OR vitamin b9*[tiab] OR Fatty acid*[tiab] OR “Fatty Acids”[Mesh:noexp] OR fatty acid*[tiab] OR “Fatty Acids, Unsaturated”[Mesh:noexp] OR Arachidonic acid*[tiab] OR linolenic acid*[tiab] OR linoleic acid*[tiab] OR Docosahexaenoic Acid*[tiab] OR Eicosapentaenoic Acid*[tiab] OR gamma-Linolenic Acid*[tiab] OR “Arachidonic Acids”[Mesh] OR “Fatty Acids, Essential”[Mesh] OR “Fatty Acids, Omega-3”[Mesh] OR “Fatty Acids, Omega-6”[Mesh] OR alpha-Linolenic Acid*[tiab] OR “Fatty Acids, Essential”[Mesh] OR “Linolenic Acids”[Mesh] OR “Trans Fatty Acids”[Mesh] OR “Fatty Acids, Monounsaturated”[Mesh] 905815

NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic[sb])

OR ((Solid food*) OR solids)); AND

OR

Nutrition*[ti] OR nutritional status[mh] OR nutritional status*[tiab] OR Nutrition Status*[tiab] OR “Child Nutrition Sciences”[majr] OR nutrient*[ti] OR “Nutritional Requirements”[Mesh]

“Vitamin B Deficiency”[Mesh] OR “Vitamins”[Mesh] OR Iron[mh] OR iron[tiab] OR “Anemia”[Mesh] OR “Anemia”[tiab] OR iron deficien*[tiab] OR ferritin*[tiab] OR ferrous[tiab] OR “Transferrin”[Mesh] OR “Transferrin”[tiab] OR zinc OR “Vitamin D”[Mesh] OR “Vitamin D”[tiab] OR “Vitamin D Deficiency”[Mesh] OR “Vitamin B 12”[Mesh] OR “Vitamin B 12”[tiab] OR “Vitamin B12”[tiab] OR “Vitamin B 12 Deficiency”[Mesh] OR Cobamide*[tiab] OR Cobalamin*[tiab] OR Cyanocobalamin[tiab] OR Folate[tiab] OR “Folic Acid”[Mesh] OR folacin[tiab] OR vitamin b9*[tiab] OR Fatty acid*[tiab] OR “Fatty Acids”[Mesh:noexp] OR fatty acid*[tiab] OR “Fatty Acids, Unsaturated”[Mesh:noexp] OR Arachidonic acid*[tiab] OR linolenic acid*[tiab] OR linoleic acid*[tiab] OR Docosahexaenoic Acid*[tiab] OR Eicosapentaenoic Acid*[tiab] OR gamma-Linolenic Acid*[tiab] OR “Arachidonic Acids”[Mesh] OR “Fatty Acids, Essential”[Mesh] OR “Fatty Acids, Omega-3”[Mesh] OR “Fatty Acids, Omega-6”[Mesh] OR alpha-Linolenic Acid*[tiab] OR “Fatty Acids, Essential”[Mesh] OR “Linolenic Acids”[Mesh] OR “Trans Fatty Acids”[Mesh] OR “Fatty Acids, Monounsaturated”[Mesh]

AND

infant* OR baby OR babies OR toddler* OR newborn*[tiab] OR “Child, Preschool”[Mesh] OR preschool*[tiab] OR pre-school*[tiab] OR “early childhood”[tiab] OR “early years”[tiab] OR pre-k[tiab] OR pre-primary[tiab] OR under five*[ti] OR young child*[ti] OR “head start”[tiab] OR prekindergarten[tiab] OR pre-kindergarten[tiab] OR weanling*

OR limit to child, preschool in PubMed?

NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic[sb])

#### Embase, Elsevier (https://www.elsevier.com/solutions/embase-biomedical-research/embase-coverage-and-content) (1947 to 9 December 2015)

Date(s) Searched: 12/9/2015

Search Terms:

(Complementary OR supplementa* OR wean* OR transition* OR introduc* OR family) NEAR/3 (feed* OR food* OR beverage* OR eating OR diet)

OR

(Complementary OR transition* OR introduct* OR wean*) AND (food/exp OR ‘baby food’/exp OR ‘cereal’/exp OR ‘dairy product’/exp OR ‘egg’/exp OR ‘fruit’/exp OR ‘meat’/exp OR ‘sea food’/exp OR ‘milk’/exp OR fish/exp OR ‘poultry’/exp OR ‘beverage’/exp OR ‘vegetable’/exp OR nut/exp OR pea/exp OR meal/exp)

OR

(Complementary OR supplementa* OR wean* OR transition* OR introduc*) NEAR/5 (‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR beverage* OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR bread* OR yog*urt* OR cheese* OR juice* OR rice OR soup OR legume* OR snack* OR meal*) (for Embase)

AND

(infant*:ti,ab OR infant/exp) OR (baby OR babies OR toddler* OR newborn* OR nurser*):ti,ab OR ‘newborn’/exp OR ‘newborn care’/exp OR preschool*:ti,ab OR pre-school:ti,ab OR ‘preschool child’/exp OR ‘infancy’/exp OR “early childhood”:ti,ab OR “early years” OR pre-k:ti,ab OR ‘nursery’/exp OR ‘nursery school’/exp OR prekindergarten:ti,ab OR pre-kindergarten:ti,ab OR weanling*

AND ([in process]/lim OR [article]/lim OR [article in press]/lim) AND ([embase]/lim NOT [medline]/lim)

AND

Limit to humans

OR

‘nutritional status’/exp OR ((nutrition* OR diet) NEAR/3 (status OR requirement* OR state)):ti,ab OR ‘nutritional requirement’/exp

OR

‘ferrous ion’/exp OR ferrous:ti,ab OR ‘iron absorption’/exp OR ‘iron deficiency anemia’/exp OR anemia:ti,ab OR ‘iron blood level’/exp OR ‘iron’/exp OR ‘ferritin’/exp OR ferritin:ti,ab OR transferrin:ti,ab OR ‘transferrin’/exp OR ‘vitamin D’/exp OR ‘vitamin D deficiency’/exp OR ‘zinc’/exp OR zinc:ti,ab OR ‘cyanocobalamin’/exp OR “vitamin d”:ti,ab OR “vitamin b12”:ti,ab OR “vitamin b 12”:ti,ab OR cyanocobalamin:ti,ab OR ‘folic acid’/exp OR ‘folic acid’:ti,ab OR folate:ti,ab OR folacin:ti,ab OR ‘cobalamin’/exp OR cobalamin*:ti,ab OR ‘cobamamide’/exp OR ‘cobamamide’:ti,ab OR cyanocobalamin*:ti,ab OR ‘fatty acid’/exp OR (fatty NEXT/1 acid*):ti,ab OR (Arachidonic acid*):ti,ab OR (linolenic NEXT/1 acid*):ti,ab OR (linoleic NEXT/1 acid*):ti,ab OR (Docosahexaenoic NEXT/1 Acid*):ti,ab OR (Eicosapentaenoic NEXT/1 Acid*):ti,ab OR (gamma-Linolenic NEXT/1 Acid*):ti,ab OR (alpha-Linolenic NEXT/1 Acid*):ti,ab

#### Cochrane Central Register of Controlled Trials (https://handbook-5-1.cochrane.org/chapter_6/6_2_1_2_the_cochrane_central_register_of_controlled_trials.htm), John Wiley & Sons in the Cochrane Library (searched August 2015)

Date(s) Searched: 12/2015

Search Terms:

(feed* OR food* OR beverage*OR diet* OR ‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR nut OR cereal OR beverage* OR bread* OR seafood OR yog*urt* OR cheese OR juice) NEAR/3 (Complementary OR supplementa* OR wean* OR transition* OR introduct* OR family)

OR

((nutrition* OR diet) NEAR/3 (status OR requirement* OR state))

AND

ferrous OR iron OR anemia OR ferritin OR zinc OR “vitamin d” OR “vitamin b12” OR “vitamin b 12” OR cyanocobalamin OR ‘folic acid’ OR folate OR folacin OR cobalamin* OR ‘cobamamide’ OR cyanocobalamin* OR (fatty NEXT/1 acid*) OR (Arachidonic acid*) OR (linolenic NEXT/1 acid*) OR (linoleic NEXT/1 acid*) OR (Docosahexaenoic NEXT/1 Acid*) OR (Eicosapentaenoic NEXT/1 Acid*) OR (gamma-Linolenic NEXT/1 Acid*) OR (alpha-Linolenic NEXT/1 Acid*)

NOT (supplement*ti,ab OR pubmed OR embase)

AND (infant* OR baby OR babies OR toddler* OR newborn* OR nurser* OR preschool* OR pre-school OR “early childhood” OR pre-k OR prekindergarten OR pre-kindergarten OR “early years”)

NOT (pubmed OR embase OR supplement*:ti OR preterm:ti)

#### CINAHL Plus with Full Text, EBSCO (https://www.ebsco.com/products/research-databases/cinahl-plus-full-text) (Cumulative Index to Nursing and Allied Health Literature; 1937 to 14 December 2015)

Date(s) Searched: 12/14/2015

Search Terms:

(MH “Food and Beverages+”) OR (MH “Food”) OR (MH “Diet”) OR (MH “Eating”) OR (MH “Eating Behavior”) OR (MH “Taste”) OR (MH “Taste Buds”) OR (MH “Cereals”) OR (MH “Dairy Products”) OR (MH “Yogurt”) OR (MH “Cheese”) OR (MH “Milk”) OR (MH “Eggs”) OR (MH “Fruit”) OR (MH “Fruit Juices”) OR (MH “Meat”) OR (MH “Seafood”) OR (MH “Fish”) OR (MH “Poultry”) OR (MH “Vegetables”) OR (MH “Nuts”) OR (MH “Legumes”) OR (MH “Bread”) AND (Complementary OR supplementa* OR wean* OR transition* OR introduc*)

OR

(‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR beverage* OR bread* OR seafood OR yog*urt* OR cheese* OR juice*) N5 (Complementary OR supplementa* OR wean* OR transition* OR introduc* OR family)

AND

(MH “Nutritional Status”) OR “nutritional status” OR (MH “Nutritional Requirements”) OR (MH “Vitamin D”) OR (MH “Vitamin D Deficiency”) OR (MH “Vitamin B12 Deficiency”) OR (MH “Anemia”) OR “anemia” OR (MH “Anemia, Iron Deficiency”) OR (MH “Iron”) OR (MH “Zinc”) OR (MH “Vitamin B12”) OR (MH “Vitamin B12 Deficiency”) OR (MH “Folic Acid”) OR (MH “Niacin”) OR (MH “Folic Acid Deficiency”) OR “folate” OR “folacin” OR cyanocobalamin* OR cobalamin* OR cobamamide* OR (MH “Fatty Acids”) OR “fatty acids” OR (MH “Fatty Acids, Omega-6”) OR (MH “Fatty Acids, Omega-3”) OR (MH “Fatty Acids, Unsaturated”) OR (MH “Trans Fatty Acids”) OR (MH “Fatty Acids, Monounsaturated”) OR (MH “Fatty Acids, Saturated”) OR (MH “Fatty Acids, Essential”) OR (MH “Arachidonic Acids”) OR (MH “Docosahexaenoic Acids”) OR (MH “Linolenic Acids”) OR (MH “Linoleic Acids”)

Limit to “all infant” OR (MH “Infant”) OR (MH “Infant, Newborn”) OR (MH “Infant Behavior”) OR (MH “Infant Feeding”) OR (MH “Infant Feeding Schedules”) OR (MH “Child, Preschool”)

Figure 2 Flow chart of literature search and screening results

Flow chart of literature search and screening results for articles examining the relationship between complementary feeding and micronutrient status. The results of an electronic database search were screened in a dual, step-wise manner by reviewing titles, abstracts, and full text articles to determine which articles met the criteria for inclusion. A manual search was done to ascertain articles not identified through the electronic database search. The SR on timing of introduction of CFB included nine articles, and the SR on types and amounts of CFB consumed included 33 articles.

Flow chart of literature search and screening results for articles examining the relationship between complementary feeding and micronutrient status. The results of an electronic database search were screened in a dual, step-wise manner by reviewing titles, abstracts, and full text articles to determine which articles met the criteria for inclusion. A manual search was done to ascertain articles not identified through the electronic database search. The systematic review on timing of introduction of CFB included nine articles, and the systematic review on types and amounts of CFB consumed included 33 articles.

### Excluded articles

The table below lists the excluded articles with at least one reason for exclusion, and may not reflect all possible reasons.

Table 4 Excluded articles

| Citation | Rationale
1 | Bioavailability of milk zinc in infants. Nutr Rev. 1984;42:220-2. | Study design, Dependent variable
2 | Nutritional findings in the U.S. preschool and young school-age population. J Bergen Cty Dent Soc. 1984;50:14-6. | Age
3 | Aboud,F. E.,Moore,A. C.,Akhter,S.. Effectiveness of a community-based responsive feeding programme in rural Bangladesh: a cluster randomized field trial. Matern Child Nutr. 2008;4:275-86. | Independent variable, Dependent variable
4 | Abrams,S. A.,O’Brien,K. O.,Wen,J.,Liang,L. K.,Stuff,J. E.. Absorption by 1-year-old children of an iron supplement given with cow’s milk or juice. Pediatr Res. 1996;39:171-5. | Independent variable, Dependent variable
5 | Abrams,S. A.,Wen,J.,Stuff,J. E.. Absorption of calcium, zinc, and iron from breast milk by five- to seven-month-old infants. Pediatr Res. 1997;41:384-90. | Study design, Independent variable
6 | Adamska,I.,Światek,K.,Czerwionka-Szaflarska,M.,Zawadzka-Gralec,A.. Influence of elimination diet on nutritional assessment in children under the age of 2 years. Pediatria Wspolczesna. 2007;9:29-36. | Dependent variable, Language
7 | Adu-Afarwuah,S.,Lartey,A.,Brown,K. H.,Zlotkin,S.,Briend,A.,Dewey,K. G.. Home fortification of complementary foods with micronutrient supplements is well accepted and has positive effects on infant iron status in Ghana. Am J Clin Nutr. 2008;87:929-38. | Country, Independent variable
8 | Agarwal,R.,Virmani,D.,Jaipal,M.,Gupta,S.,Sankar,M. J.,Bhatia,S.,Agarwal,A.,Devgan,V.,Deorari,A.,Paul,V. K.,Toteja,G. S.. Poor zinc status in early infancy among both low and normal birth weight infants and their mothers in Delhi. Neonatology. 2013;103:54-9. | Country, Independent variable
9 | Agostoni,C.,Marangoni,F.,Giovannini,M.,Galli,C.,Riva,E.. Prolonged breast-feeding (six months or more) and milk fat content at six months are associated with higher developmental scores at one year of age within a breast-fed population. Adv Exp Med Biol. 2001;501:137-41. | Independent variable
10 | Agostoni,C.,Riva,E.. Dietary fatty acids and cholesterol in the first 2 years of life. Prostaglandins Leukot Essent Fatty Acids. 1998;58:33-7. | Study design
11 | Agostoni,C.,Trojan,S.,Bellu,R.,Riva,E.,Bruzzese,M. G.,Giovannini,M.. Developmental quotient at 24 months and fatty acid composition of diet in early infancy: a follow up study. Arch Dis Child. 1997;76:421-4. | Independent variable, Dependent variable
12 | Agustina,R.,Bovee-Oudenhoven,I. M.,Lukito,W.,Fahmida,U.,van de Rest,O.,Zimmermann,M. B.,Firmansyah,A.,Wulanti,R.,Albers,R.,van den Heuvel,E. G.,Kok,F. J.. Probiotics Lactobacillus reuteri DSM 17938 and Lactobacillus casei CRL 431 modestly increase growth, but not iron and zinc status, among Indonesian children aged 1-6 years. J Nutr. 2013;143:1184-93. | Age, Country, Independent variable
13 | Al-Alawi,M.,Sarhan,N.. Prevalence of anemia among nine-month-old infants attending primary care in Bahrain. Journal of the Bahrain Medical Society. 2014;25:29-32. | Study design, Independent variable
14 | Al-Atawi,M. S.,Al-Alwan,I. A.,Al-Mutair,A. N.,Tamim,H. M.,Al-Jurayyan,N. A.. Epidemiology of nutritional rickets in children. Saudi J Kidney Dis Transpl. 2009;20:260-5. | Study design, Independent variable
15 | Alexy,U.,Kersting,M.,Sichert-Hellert,W.,Manz,F.,Schoch,G.. Energy intake and growth of 3- to 36-month-old German infants and children. Ann Nutr Metab. 1998;42:68-74. | Independent variable, Dependent variable
16 | Almquist-Tangen,G.,Dahlgren,J.,Roswall,J.,Bergman,S.,Alm,B.. Milk cereal drink increases BMI risk at 12 and 18 months, but formula does not. Acta Paediatr. 2013;102:1174-9. | Dependent variable
17 | Almqvist,C.,Garden,F.,Xuan,W.,Mihrshahi,S.,Leeder,S. R.,Oddy,W.,Webb,K.,Marks,G. B.. Omega-3 and omega-6 fatty acid exposure from early life does not affect atopy and asthma at age 5 years. J Allergy Clin Immunol. 2007;119:1438-44. | Independent variable, Dependent variable
18 | Altucher,K.,Rasmussen,K. M.,Barden,E. M.,Habicht,J. P.. Predictors of improvement in hemoglobin concentration among toddlers enrolled in the Massachusetts WIC Program. J Am Diet Assoc. 2005;105:709-15. | Independent variable, Dependent variable
19 | Anand,K.,Lakshmy,R.,Janakarajan,V. N.,Ritvik,A.,Misra,P.,Pandey,R. M.,Kapoor,S. K.,Sankar,R.,Bulusu,S.. Effect of consumption of micronutrient fortified candies on the iron and vitamin A status of children aged 3-6 years in rural Haryana. Indian Pediatr. 2007;44:823-9. | Age, Independent variable
20 | Andersen,A. D.,Michaelsen,K. F.,Hellgren,L. I.,Trolle,E.,Lauritzen,L.. A randomized controlled intervention with fish oil versus sunflower oil from 9 to 18 months of age: exploring changes in growth and skinfold thicknesses. Pediatr Res. 2011;70:368-74. | Independent variable
21 | Andersen,L. B.,Pipper,C. B.,Trolle,E.,Bro,R.,Larnkjaer,A.,Carlsen,E. M.,Molgaard,C.,Michaelsen,K. F.. Maternal obesity and offspring dietary patterns at 9 months of age. Eur J Clin Nutr. 2015;69:668-75. | Dependent variable
22 | Anfield,L.. Nutrition in the first year. Midwife Health Visit Community Nurse. 1985;21:161-4. | Study design
23 | Antunes,H.,Santos,C.,Carvalho,S.,Gonçalves,S.,Costa-Pereira,A.. Male gender is an important clinical risk factor for iron deficiency in healthy infants. e-SPEN Journal. 2012;7:e219-e222. | Study design, Independent variable
24 | Arsenault,J. E.,Lopez de Romana,D.,Penny,M. E.,Van Loan,M. D.,Brown,K. H.. Additional zinc delivered in a liquid supplement, but not in a fortified porridge, increased fat-free mass accrual among young Peruvian children with mild-to-moderate stunting. J Nutr. 2008;138:108-14. | Health Status
25 | Arvas,A.,Elgormus,Y.,Gur,E.,Alikasifoglu,M.,Celebi,A.. Iron status in breast-fed full-term infants. Turk J Pediatr. 2000;42:22-6. | Independent variable
26 | Ayer,J. G.,Harmer,J. A.,Xuan,W.,Toelle,B.,Webb,K.,Almqvist,C.,Marks,G. B.,Celermajer,D. S.. Dietary supplementation with n-3 polyunsaturated fatty acids in early childhood: effects on blood pressure and arterial structure and function at age 8 y. Am J Clin Nutr. 2009;90:438-46. | Age
27 | Baatenburg de Jong,R.,Bekhof,J.,Roorda,R.,Zwart,P.. Severe nutritional vitamin deficiency in a breast-fed infant of a vegan mother. Eur J Pediatr. 2005;164:259-60. | Study design
28 | Bakker,E. C.,van Houwelingen,A. C.,Hornstra,G.. Early nutrition, essential fatty acid status and visual acuity of term infants at 7 months of age. Eur J Clin Nutr. 1999;53:872-9. | Study design
29 | Balogun,T. A.,Lombard,M. J.,McLachlan,M.. The nutrient intake of children aged 12-36 months living in two communities in the Breede Valley, Western Cape province, South Africa. South African Family Practice. 2015;57:1-7 7p. | Study design, Country
30 | Bamji,M. S.,Chowdhury,N.,Ramalakshmi,B. A.,Jacob,C. M.. Enzymatic evaluation of riboflavin status of infants. Eur J Clin Nutr. 1991;45:309-13. | Study design
31 | Baptist,E. C.,Castillo,S. F.. Cow’s milk-induced iron deficiency anemia as a cause of childhood stroke. Clin Pediatr (Phila). 2002;41:533-5. | Study design
32 | Begin,F.,Santizo,M. C.,Peerson,J. M.,Torun,B.,Brown,K. H.. Effects of bovine serum concentrate, with or without supplemental micronutrients, on the growth, morbidity, and micronutrient status of young children in a low-income, peri-urban Guatemalan community. Eur J Clin Nutr. 2008;62:39-50. | Independent variable
33 | Beinner,M. A.,Lamounier,J. A.,Tomaz,C.. Effect of iron-fortified drinking water of daycare facilities on the hemoglobin status of young children. J Am Coll Nutr. 2005;24:107-14. | Age, Independent variable
34 | Beinner,M. A.,Velasquez-Melendez,G.,Pessoa,M. C.,Greiner,T.. Iron-fortified rice is as efficacious as supplemental iron drops in infants and young children. J Nutr. 2010;140:49-53. | Health Status, Independent variable
35 | Ben,X. M.,Zhou,X. Y.,Zhao,W. H.,Yu,W. L.,Pan,W.,Zhang,W. L.,Wu,S. M.,Van Beusekom,C. M.,Schaafsma,A.. Growth and development of term infants fed with milk with long-chain polyunsaturated fatty acid supplementation. Chin Med J (Engl). 2004;117:1268-70. | Independent variable
36 | Bentley,M. E.,Caulfield,L. E.,Ram,M.,Santizo,M. C.,Hurtado,E.,Rivera,J. A.,Ruel,M. T.,Brown,K. H.. Zinc supplementation affects the activity patterns of rural Guatemalan infants. J Nutr. 1997;127:1333-8. | Independent variable
37 | Berger,J.,Ninh,N. X.,Khan,N. C.,Nhien,N. V.,Lien,D. K.,Trung,N. Q.,Khoi,H. H.. Efficacy of combined iron and zinc supplementation on micronutrient status and growth in Vietnamese infants. Eur J Clin Nutr. 2006;60:443-54. | Country, Independent variable
38 | Bernal,M. J.,Periago,M. J.,Martinez,R.,Ortuno,I.,Sanchez-Solis,M.,Ros,G.,Romero,F.,Abellan,P.. Effects of infant cereals with different carbohydrate profiles on colonic function--randomised and double-blind clinical trial in infants aged between 6 and 12 months--pilot study. Eur J Pediatr. 2013;172:1535-42. | Independent variable, Dependent variable
39 | Bilenko,N.,Fraser,D.,Vardy,H.,Belmaker,I.. Impact of multiple micronutrient supplementation (“sprinkles”) on iron deficiency anemia in Bedouin Arab and Jewish infants. Isr Med Assoc J. 2014;16:434-8. | Independent variable
40 | Birch,E. E.,Garfield,S.,Hoffman,D. R.,Uauy,R.,Birch,D. G.. A randomized controlled trial of early dietary supply of long-chain polyunsaturated fatty acids and mental development in term infants. Dev Med Child Neurol. 2000;42:174-81. | Independent variable
41 | Birch,E. E.,Hoffman,D. R.,Uauy,R.,Birch,D. G.,Prestidge,C.. Visual acuity and the essentiality of docosahexaenoic acid and arachidonic acid in the diet of term infants. Pediatr Res. 1998;44:201-9. | Independent variable
42 | Birkbeck,J. A.,Scott,H. F.. 25-Hydroxycholecalciferol serum levels in breast-fed infants. Arch Dis Child. 1980;55:691-5. | Independent variable
43 | Birlouez-Aragon,I.,Rivière,S.,Bailly,L.,Burban,Y.,Dardenne,A.,Pertuis,S.. Restoration of nutritional balance in children between 6 and 8 years of age. Journal de Pediatrie et de Puericulture. 1998;11:98-103. | Age, Language
44 | Black,A. P.,Vally,H.,Morris,P.,Daniel,M.,Esterman,A.,Smith,F.,O’Dea,K.. High folate levels in Aboriginal children after subsidised fruit and vegetables and mandatory folic acid fortification. Aust N Z J Public Health. 2014;38:241-6. | Study design, Age
45 | Block,S. L.. Delayed introduction of solid foods to infants: not so fast!. Pediatr Ann. 2013;42:143-7. | Study design
46 | Bloem,M. W.,Wedel,M.,Egger,R. J.,Speek,A. J.,Schrijver,J.,Saowakontha,S.,Schreurs,W. H.. Iron metabolism and vitamin A deficiency in children in northeast Thailand. Am J Clin Nutr. 1989;50:332-8. | Health Status
47 | Bogard,J. R.,Hother,A. L.,Saha,M.,Bose,S.,Kabir,H.,Marks,G. C.,Thilsted,S. H.. Inclusion of Small Indigenous Fish Improves Nutritional Quality During the First 1000 Days. Food Nutr Bull. 2015;36:276-89. | Dependent variable
48 | Bortolini,G. A.,Vitolo,M. R.. The impact of systematic dietary counseling during the first year of life on prevalence rates of anemia and iron deficiency at 12-16 months. J Pediatr (Rio J). 2012;88:33-9. | Independent variable
49 | Brady,H.,Lamb,M. M.,Sokol,R. J.,Ross,C. A.,Seifert,J. A.,Rewers,M. J.,Norris,J. M.. Plasma micronutrients are associated with dietary intake and environmental tobacco smoke exposure in a paediatric population. Public Health Nutr. 2007;10:712-8. | Age, Independent variable
50 | Briend,A.,Bari,A.. Breastfeeding improves survival, but not nutritional status, of 12-35 months old children in rural Bangladesh. Eur J Clin Nutr. 1989;43:603-8. | Country, Independent variable, Dependent variable
51 | Brito,A.,Olivares,M.,Pizarro,T.,Rodriguez,L.,Hertrampf,E.. Chilean complementary feeding program reduces anemia and improves iron status in children aged 11 to 18 months. Food Nutr Bull. 2013;34:378-85. | Study design
52 | Brooke,O. G.. Supplementary vitamin D in infancy and childhood. Arch Dis Child. 1983;58:573-4. | Study design
53 | Brown,K. H.,Lopez de Romana,D.,Arsenault,J. E.,Peerson,J. M.,Penny,M. E.. Comparison of the effects of zinc delivered in a fortified food or a liquid supplement on the growth, morbidity, and plasma zinc concentrations of young Peruvian children. Am J Clin Nutr. 2007;85:538-47. | Independent variable
54 | Brunskill,A. J.,Ng,K. T.. The prevalence of and antecedents to iron deficiency in infants in a Victorian shire. Community Health Stud. 1986;10:167-72. | Study design, Independent variable
55 | Brunt,Deborah R.,Grant,Cameron C.,Wall,Clare R.,Reed,Peter W.. Interaction between risk factors for iron deficiency in young children. Nutrition & Dietetics. 2012;69:285-292 8p. | Study design
56 | Calvo,E. B.,Galindo,A. C.,Aspres,N. B.. Iron status in exclusively breast-fed infants. Pediatrics. 1992;90:375-9. | Independent variable
57 | Calvo,E. B.,Gnazzo,N.. Prevalence of iron deficiency in children aged 9-24 mo from a large urban area of Argentina. Am J Clin Nutr. 1990;52:534-40. | Study design, Independent variable
58 | Calvo,E.,Hertrampf,E.,Pablo,S.,Amar,M.,Stekel,A.. Haemoglobin-fortified cereal: an alternative weaning food with high iron bioavailability. European journal of clinical nutrition. 1989;43:237-43. | Independent variable, Dependent variable
59 | Cameron,S. L.,Taylor,R. W.,Heath,A. L.. Development and pilot testing of Baby-Led Introduction to SolidS--a version of Baby-Led Weaning modified to address concerns about iron deficiency, growth faltering and choking. BMC Pediatr. 2015;15:99. | Independent variable, Dependent variable
60 | Capozzi,L.,Russo,R.,Bertocco,F.,Ferrara,D.,Ferrara,M.. Diet and iron deficiency in the first year of life: a retrospective study. Hematology. 2010;15:410-3. | Study design, Independent variable
61 | Capozzi,L.,Russo,R.,Bertocco,F.,Ferrara,D.,Ferrara,M.. Effect on haematological and anthropometric parameters of iron supplementation in the first 2 years of life. Risks and benefits. Hematology. 2011;16:261-4. | Independent variable
62 | Carruth,B. R.,Nevling,W.,Skinner,J. D.. Developmental and food profiles of infants born to adolescent and adult mothers. J Adolesc Health. 1997;20:434-41. | Independent variable, Dependent variable
63 | Chang,S.,Huang,Z.,Ma,Y.,Piao,J.,Yang,X.,Zeder,C.,Hurrell,R. F.,Egli,I.. Mixture of ferric sodium ethylenediaminetetraacetate (NaFeEDTA) and ferrous sulfate: an effective iron fortificant for complementary foods for young Chinese children. Food Nutr Bull. 2012;33:111-6. | Age
64 | Chang,Y.,Zhai,F.,Li,W.,Ge,K.,Jin,D.,de Onis,M.. Nutritional status of preschool children in poor rural areas of China. Bull World Health Organ. 1994;72:105-12. | Study design, Age
65 | Chavasit,V.,Porasuphatana,S.,Suthutvoravut,U.,Zeder,C.,Hurrell,R.. Iron bioavailability in 8-24-month-old Thai children from a micronutrient-fortified quick-cooking rice containing ferric ammonium citrate or a mixture of ferrous sulphate and ferric sodium ethylenediaminetetraacetic acid. Maternal and Child Nutrition. 2015. | Dependent variable
66 | Chawla,P.,Puri,R.. Impact of pre-school supplementary feeding on clinical picture. Indian Pediatr. 1983;20:507-12. | Study design, Age
67 | Chierici,R.,Sawatzki,G.,Tamisari,L.,Volpato,S.,Vigi,V.. Supplementation of an adapted formula with bovine lactoferrin. 2. Effects on serum iron, ferritin and zinc levels. Acta Paediatr. 1992;81:475-9. | Independent variable
68 | Childs,F.,Aukett,A.,Darbyshire,P.,Ilett,S.,Livera,L. N.. Dietary education and iron deficiency anaemia in the inner city. Arch Dis Child. 1997;76:144-7. | Independent variable, Dependent variable
69 | Chirmulay,D.,Nisal,R.. Nutritional status of tribal underfive children in Ahmadnagar District, Maharashtra in relation to weaning/feeding practices. Indian Pediatr. 1993;30:215-22. | Study design, Age, Country
70 | Chmielewska,A.,Chmielewski,G.,Domellof,M.,Lewandowski,Z.,Szajewska,H.. Effect of iron supplementation on psychomotor development of non-anaemic, exclusively or predominantly breastfed infants: a randomised, controlled trial. BMJ Open. 2015;5:e009441. | Study design, Independent variable
71 | Chorell,E.,Karlsson Videhult,F.,Hernell,O.,Antti,H.,West,C. E.. Impact of probiotic feeding during weaning on the serum lipid profile and plasma metabolome in infants. Br J Nutr. 2013;110:116-26. | Independent variable, Dependent variable
72 | Christofides,A.,Schauer,C.,Zlotkin,S. H.. Iron deficiency and anemia prevalence and associated etiologic risk factors in First Nations and Inuit communities in Northern Ontario and Nunavut. Can J Public Health. 2005;96:304-7. | Study design
73 | Cook,J. D.,Reddy,M. B.,Burri,J.,Juillerat,M. A.,Hurrell,R. F.. The influence of different cereal grains on iron absorption from infant cereal foods. Am J Clin Nutr. 1997;65:964-9. | Independent variable, Dependent variable
74 | Cortese,M.,Riise,T.,Bjørnevik,K.,Holmøy,T.,Kampman,M. T.,Magalhaes,S.,Pugliatti,M.,Wolfson,C.,Myhr,K. M.. Timing of use of cod liver oil, a vitamin D source, and multiple sclerosis risk: The EnvIMS study. Multiple Sclerosis. 2015;21:1856-1864. | Age, Independent variable, Dependent variable
75 | Cosenza,L.,Pezzella,V.,Nocerino,R.,Di Costanzo,M.,Coruzzo,A.,Passariello,A.,Leone,L.,Savoia,M.,Del Puente,A.,Esposito,A.,Terrin,G.,Berni Canani,R.. Calcium and vitamin D intakes in children: a randomized controlled trial. BMC Pediatr. 2013;13:86. | Age, Independent variable
76 | Costa,A.,Oliveira,P.. About iron deficiency in early childhood. Nascer e Crescer. 2003;12:74-79. | Language
77 | Dagnelie,P. C.,van Staveren,W. A.,Vergote,F. J.,Dingjan,P. G.,van den Berg,H.,Hautvast,J. G.. Increased risk of vitamin B-12 and iron deficiency in infants on macrobiotic diets. Am J Clin Nutr. 1989;50:818-24. | Study design
78 | Dagnelie,P. C.,van Staveren,W. A.,Verschuren,S. A.,Hautvast,J. G.. Nutritional status of infants aged 4 to 18 months on macrobiotic diets and matched omnivorous control infants: a population-based mixed-longitudinal study. I. Weaning pattern, energy and nutrient intake. Eur J Clin Nutr. 1989;43:311-23. | Study design
79 | Dallman,P. R.. Inhibition of iron absorption by certain foods. Am J Dis Child. 1980;134:453-4. | Study design, Dependent variable
80 | Dalton,M. A.,Sargent,J. D.,O’Connor,G. T.,Olmstead,E. M.,Klein,R. Z.. Calcium and phosphorus supplementation of iron-fortified infant formula: no effect on iron status of healthy full-term infants. Am J Clin Nutr. 1997;65:921-6. | Independent variable
81 | Davidsson,L.,Jamil,K. A.,Sarker,S. A.,Zeder,C.,Fuchs,G.,Hurrell,R.. Human milk as a source of ascorbic acid: no enhancing effect on iron bioavailability from a traditional complementary food consumed by Bangladeshi infants and young children. Am J Clin Nutr. 2004;79:1073-7. | Country, Independent variable
82 | Davidsson,L.,Mackenzie,J.,Kastenmayer,P.,Aggett,P. J.,Hurrell,R. F.. Zinc and calcium apparent absorption from an infant cereal: a stable isotope study in healthy infants. Br J Nutr. 1996;75:291-300. | Independent variable, Dependent variable
83 | Davidsson,L.,Sarker,S. A.,Jamil,K. A.,Sultana,S.,Hurrell,R.. Regular consumption of a complementary food fortified with ascorbic acid and ferrous fumarate or ferric pyrophosphate is as useful as ferrous sulfate in maintaining hemoglobin concentrations >105 g/L in young Bangladeshi children. Am J Clin Nutr. 2009;89:1815-20. | Independent variable
84 | Davis,J. R.,Jr.,Goldenring,J.,Lubin,B. H.. Nutritional vitamin B12 deficiency in infants. Am J Dis Child. 1981;135:566-7. | Study design
85 | Dawodu,A.,Davidson,B.,Woo,J. G.,Peng,Y. M.,Ruiz-Palacios,G. M.,de Lourdes Guerrero,M.,Morrow,A. L.. Sun exposure and vitamin D supplementation in relation to vitamin D status of breastfeeding mothers and infants in the global exploration of human milk study. Nutrients. 2015;7:1081-93. | Independent variable
86 | de Almeida,C. A.,Dutra-De-Oliveira,J. E.,Crott,G. C.,Cantolini,A.,Ricco,R. G.,Del Ciampo,L. A.,Baptista,M. E.. Effect of fortification of drinking water with iron plus ascorbic acid or with ascorbic acid alone on hemoglobin values and anthropometric indicators in preschool children in day-care centers in Southeast Brazil. Food Nutr Bull. 2005;26:259-65. | Age, Independent variable
87 | de Freitas,C. L.,Romani,S.,Amigo,H.. Breast-feeding and malnutrition in rural areas of northeast Brazil. Bull Pan Am Health Organ. 1986;20:138-46. | Study design, Independent variable, Dependent variable
88 | Deegan,K. L.,Jones,K. M.,Zuleta,C.,Ramirez-Zea,M.,Lildballe,D. L.,Nexo,E.,Allen,L. H.. Breast milk vitamin B-12 concentrations in Guatemalan women are correlated with maternal but not infant vitamin B-12 status at 12 months postpartum. J Nutr. 2012;142:112-6. | Independent variable
89 | Delgado,H. L.,Martorell,R.,Klein,R. E.. Nutrition, lactation, and birth interval components in rural Guatemala. Am J Clin Nutr. 1982;35:1468-76. | Country, Dependent variable
90 | Dewey,K. G.,Cohen,R. J.,Brown,K. H.,Rivera,L. L.. Effects of exclusive breastfeeding for four versus six months on maternal nutritional status and infant motor development: results of two randomized trials in Honduras. J Nutr. 2001;131:262-7. | Dependent variable
91 | Dewey,K. G.,Cohen,R. J.,Rivera,L. L.,Brown,K. H.. Effects of age of introduction of complementary foods on iron status of breast-fed infants in Honduras. Am J Clin Nutr. 1998;67:878-84. | Country
92 | Dewey,K. G.,Domellof,M.,Cohen,R. J.,Landa Rivera,L.,Hernell,O.,Lonnerdal,B.. Iron supplementation affects growth and morbidity of breast-fed infants: results of a randomized trial in Sweden and Honduras. J Nutr. 2002;132:3249-55. | Independent variable
93 | Dewey,K. G.,Huffman,S. L.. Maternal, infant, and young child nutrition: combining efforts to maximize impacts on child growth and micronutrient status. Food Nutr Bull. 2009;30:S187-9. | Study design
94 | Dewey,K. G.,Lonnerdal,B.. Milk and nutrient intake of breast-fed infants from 1 to 6 months: relation to growth and fatness. J Pediatr Gastroenterol Nutr. 1983;2:497-506. | Dependent variable
95 | Dewey,K. G.,Reinhart,G. A.. Introduction. Fatty acid status in early life in low-income countries: determinants & consequences. Matern Child Nutr. 2011;7 Suppl 2:1. | Study design
96 | Dewey,K. G.,Romero-Abal,M. E.,Quan de Serrano,J.,Bulux,J.,Peerson,J. M.,Eagle,P.,Solomons,N. W.. Effects of discontinuing coffee intake on iron status of iron-deficient Guatemalan toddlers: a randomized intervention study. Am J Clin Nutr. 1997;66:168-76. | Country
97 | Dewey,K.. Meeting protein needs at 6 to 24 months of age. Food Nutr Bull. 2013;34:240-1. | Study design
98 | Diana,L. Culbertson Jamie L. Westcott Laurie Sherlock K. Michael Hambidge Nancy F. Krebs. Zinc (Zn) Intake from Different Complementary Feeding (CF) Regimens. Pediatric Academic Societies Annual Meeting. 2011. | Study design
99 | Dickson,N.,Morison,I.. Iron deficiency in infants of Cambodian refugees. N Z Med J. 1992;105:83-4. | Study design, Country
100 | Dine,M. S.. Evaluation of the free erythrocyte porphyrin (FEP) test in a private practice: the incidence of iron deficiency and increased lead absorption in 9- to 13-month-old infants. Pediatrics. 1980;65:303-6. | Study design
101 | Domellof,M.,Cohen,R. J.,Dewey,K. G.,Hernell,O.,Rivera,L. L.,Lonnerdal,B.. Iron supplementation of breast-fed Honduran and Swedish infants from 4 to 9 months of age. J Pediatr. 2001;138:679-87. | Independent variable
102 | Domellof,M.,Lonnerdal,B.,Abrams,S. A.,Hernell,O.. Iron absorption in breast-fed infants: effects of age, iron status, iron supplements, and complementary foods. Am J Clin Nutr. 2002;76:198-204. | Independent variable, Dependent variable
103 | Domellof,M.,Lonnerdal,B.,Dewey,K. G.,Cohen,R. J.,Rivera,L. L.,Hernell,O.. Sex differences in iron status during infancy. Pediatrics. 2002;110:545-52. | Independent variable
104 | Dong,C.,Ge,P.,Ren,X.,Wang,J.,Fan,H.,Yan,X.,Yin,S. A.. Prospective study on the effectiveness of complementary food supplements on improving status of elder infants and young children in the areas affected by Wenchuan earthquake. PLoS One. 2013;8:e72711. | Study design, Health Status
105 | Dong,C.,Ge,P.,Ren,X.,Zhao,X.,Wang,J.,Fan,H.,Yin,S. A.. Growth and anaemia among infants and young children for two years after the Wenchuan earthquake. Asia Pac J Clin Nutr. 2014;23:445-51. | Study design, Health Status
106 | Dorea,J. G.,Furumoto,R. A.. Infant feeding practices among poor families of an urban squatter community. Ann Nutr Metab. 1992;36:257-64. | Study design, Dependent variable
107 | Doron,D.,Hershkop,K.,Granot,E.. Nutritional deficits resulting from an almond-based infant diet. Clin Nutr. 2001;20:259-61. | Study design
108 | Du Plessis,L. M.,Kruger,H. S.,Sweet,L.. Complementary feeding: a critical window of opportunity from six months onwards. South African Journal of Clinical Nutrition. 2013;26:S129-40 1p. | Study design
109 | Dube,K.,Schwartz,J.,Mueller,M. J.,Kalhoff,H.,Kersting,M.. Iron intake and iron status in breastfed infants during the first year of life. Clin Nutr. 2010;29:773-8. | Independent variable
110 | Duggan,C.,Penny,M. E.,Hibberd,P.,Gil,A.,Huapaya,A.,Cooper,A.,Coletta,F.,Emenhiser,C.,Kleinman,R. E.. Oligofructose-supplemented infant cereal: 2 randomized, blinded, community-based trials in Peruvian infants. Am J Clin Nutr. 2003;77:937-42. | Independent variable
111 | Dunne,A.. Nutrition in infancy: achieving nutrition needs for new mothers and children. Br J Community Nurs. 2012;Suppl:S22. | Study design
112 | Durnin,J. V.,Aitchison,T. C.,Beckett,C.,Husaini,M.,Pollitt,E.. Nutritional intake of an undernourished infant population receiving an energy and micronutrient supplement in Indonesia. Eur J Clin Nutr. 2000;54 Suppl 2:S43-51. | Country, Health Status, Independent variable
113 | Dutra-de-Oliveira,J. E.,Lamounier,J. A.,de Almeida,C. A.,Marchini,J. S.. Fortification of drinking water to control iron-deficiency anemia in preschool children. Food Nutr Bull. 2007;28:173-80. | Age, Independent variable
114 | D’Vaz,N.,Meldrum,S. J.,Dunstan,J. A.,Martino,D.,McCarthy,S.,Metcalfe,J.,Tulic,M. K.,Mori,T. A.,Prescott,S. L.. Postnatal fish oil supplementation in high-risk infants to prevent allergy: randomized controlled trial. Pediatrics. 2012;130:674-82. | Independent variable
115 | Ekbote,V. H.,Khadilkar,A. V.,Chiplonkar,S. A.,Hanumante,N. M.,Khadilkar,V. V.,Mughal,M. Z.. A pilot randomized controlled trial of oral calcium and vitamin D supplementation using fortified laddoos in underprivileged Indian toddlers. Eur J Clin Nutr. 2011;65:440-6. | Age
116 | Elalfy,M. S.,Hamdy,A. M.,Maksoud,S. S.,Megeed,R. I.. Pattern of milk feeding and family size as risk factors for iron deficiency anemia among poor Egyptian infants 6 to 24 months old. Nutr Res. 2012;32:93-9. | Study design, Country
117 | Emmett,P. M.,Jones,L. R.. Diet and growth in infancy: relationship to socioeconomic background and to health and development in the Avon Longitudinal Study of Parents and Children. Nutr Rev. 2014;72:483-506. | Study design, Independent variable, Dependent variable
118 | Eneroth,H.,El Arifeen,S.,Persson,L. A.,Kabir,I.,Lonnerdal,B.,Hossain,M. B.,Ekstrom,E. C.. Duration of exclusive breast-feeding and infant iron and zinc status in rural Bangladesh. J Nutr. 2009;139:1562-7. | Country, Independent variable
119 | Eneroth,H.,El Arifeen,S.,Persson,L. A.,Lonnerdal,B.,Hossain,M. B.,Stephensen,C. B.,Ekstrom,E. C.. Maternal multiple micronutrient supplementation has limited impact on micronutrient status of Bangladeshi infants compared with standard iron and folic acid supplementation. J Nutr. 2010;140:618-24. | Country, Independent variable
120 | Eneroth,H.,Persson,L. A.,El Arifeen,S.,Ekstrom,E. C.. Infant anaemia is associated with infection, low birthweight and iron deficiency in rural Bangladesh. Acta Paediatr. 2011;100:220-5. | Country, Independent variable
121 | Engelmann,M. D.,Davidsson,L.,Sandstrom,B.,Walczyk,T.,Hurrell,R. F.,Michaelsen,K. F.. The influence of meat on nonheme iron absorption in infants. Pediatr Res.. 1998;43:768-73. | Independent variable, Dependent variable
122 | Faber,M.,Benade,A. J.. Perceptions of infant cereals and dietary intakes of children aged 4-24 months in a rural South African community. Int J Food Sci Nutr. 2001;52:359-65. | Study design, Country, Dependent variable
123 | Faber,M.,Kvalsvig,J. D.,Lombard,C. J.,Benade,A. J.. Effect of a fortified maize-meal porridge on anemia, micronutrient status, and motor development of infants. Am J Clin Nutr. 2005;82:1032-9. | Country, Health Status, Independent variable
124 | Faber,M.. Dietary intake and anthropometric status differ for anaemic and non-anaemic rural South African infants aged 6-12 months. J Health Popul Nutr. 2007;25:285-93. | Study design, Country
125 | Fahmida,U.,Kolopaking,R.,Santika,O.,Sriani,S.,Umar,J.,Htet,M. K.,Ferguson,E.. Effectiveness in improving knowledge, practices, and intakes of “key problem nutrients” of a complementary feeding intervention developed by using linear programming: experience in Lombok, Indonesia. Am J Clin Nutr. 2015;101:455-61. | Dependent variable
126 | Fairweather-Tait,S. J.,Wharf,S. G.,Fox,T. E.. Zinc absorption in infants fed iron-fortified weaning food. Am J Clin Nutr. 1995;62:785-9. | Independent variable, Dependent variable
127 | Fairweather-Tait,S.,Fox,T.,Wharf,S. G.,Eagles,J.. The bioavailability of iron in different weaning foods and the enhancing effect of a fruit drink containing ascorbic acid. Pediatr Res. 1995;37:389-94. | Independent variable, Dependent variable
128 | Fawzi,W. W.,Forman,M. R.,Levy,A.,Graubard,B. I.,Naggan,L.,Berendes,H. W.. Maternal anthropometry and infant feeding practices in Israel in relation to growth in infancy: the North African Infant Feeding Study. Am J Clin Nutr. 1997;65:1731-7. | Dependent variable
129 | Fawzi,W. W.,Herrera,M. G.,Nestel,P.,el Amin,A.,Mohamed,K. A.. A longitudinal study of prolonged breastfeeding in relation to child undernutrition. Int J Epidemiol. 1998;27:255-60. | Country, Dependent variable
130 | Ferrara,M.,Bertocco,F.,Ricciardi,A.,Ferrara,D.,Incarnato,L.,Capozzi,L.. Iron deficiency screening in the first three years of life: a three-decade-long retrospective case study. Hematology. 2014;19:239-43. | Study design
131 | Ferraz,I. S.,Daneluzzi,J. C.,Vannucchi,H.. Vitamin A deficiency in children aged 6 to 24 months in Sao Paulo State, Brazil. Nutrition Research. 2000;20:757-768. | Independent variable, Dependent variable
132 | Ferris,A. G.,Laus,M. J.,Hosmer,D. W.,Beal,V. A.. The effect of diet on weight gain in infancy. Am J Clin Nutr. 1980;33:2635-42. | Dependent variable
133 | Fewtrell,M.. 2.4 Complementary foods. World Rev Nutr Diet. 2015;113:109-12. | Study design
134 | Fildes,V.. Weaning: on the bottle again. Nurs Mirror. 1980;151:18-21. | Study design
135 | Fomon,S. J.,Ziegler,E. E.,Nelson,S. E.,Edwards,B. B.. Cow milk feeding in infancy: gastrointestinal blood loss and iron nutritional status. J Pediatr. 1981;98:540-5. | Independent variable
136 | Fomon,S. J.. Bioavailability of supplemental iron in commercially prepared dry infant cereals. J Pediatr. 1987;110:660-1. | Study design, Dependent variable
137 | Fomon,S. J.. Feeding normal infants: rationale for recommendations. J Am Diet Assoc. 2001;101:1002-5. | Study design
138 | Forsyth,S.. Meeting nutrient needs in the first 1,000 days of life. Ann Nutr Metab. 2014;65:2-3. | Study design
139 | Friel,J. K.,Andrews,W. L.,Simmons,B. S.,L’Abbe,M. R.,Mercer,C.,MacDonald,A.,McCloy,U. R.. Evaluation of full-term infants fed an evaporated milk formula. Acta Paediatr. 1997;86:448-53. | Independent variable
140 | Frontela,C.,Scarino,M. L.,Ferruzza,S.,Ros,G.,Martinez,C.. Effect of dephytinization on bioavailability of iron, calcium and zinc from infant cereals assessed in the Caco-2 cell model. World J Gastroenterol. 2009;15:1977-84. | Study design, Health Status
141 | Gallo,S.,Comeau,K.,Vanstone,C.,Agellon,S.,Sharma,A.,Jones,G.,L’Abbe,M.,Khamessan,A.,Rodd,C.,Weiler,H.. Effect of different dosages of oral vitamin D supplementation on vitamin D status in healthy, breastfed infants: a randomized trial. Jama. 2013;309:1785-92. | Independent variable
142 | Gan,C. Y.,Chin,B.,Teoh,S. T.,Chan,M. K.. Nutritional status of Kadazan children in a rural district in Sabah, Malaysia. Southeast Asian J Trop Med Public Health. 1993;24:293-301. | Study design, Age
143 | Garry,P. J.,Owen,G. M.,Hooper,E. M.,Gilbert,B. A.. Iron absorption from human milk and formula with and without iron supplementation. Pediatr Res. 1981;15:822-8. | Independent variable
144 | Gibson,R. S.,Hotz,C.. The adequacy of micronutrients in complementary foods. Pediatrics. 2000;106:1298-9. | Study design
145 | Gibson,S.,Sidnell,A.. Nutrient adequacy and imbalance among young children aged 1-3 years in the UK. Nutrition Bulletin. 2013;39:172-180 9p. | Study design
146 | Glinz,D.,Hurrell,R. F.,Ouattara,M.,Zimmermann,M. B.,Brittenham,G. M.,Adiossan,L. G.,Righetti,A. A.,Seifert,B.,Diakité,V. G.,Utzinger,J.,N’Goran,E. K.,Wegmüller,R.. The effect of iron-fortified complementary food and intermittent preventive treatment of malaria on anaemia in 12- to 36-month-old children: A cluster-randomised controlled trial. Malaria Journal. 2015;14. | Country, Independent variable
147 | Godel,J. C.,Pabst,H. F.,Hodges,P. E.,Johnson,K. E.. Iron status and pregnancy in a northern Canadian population: relationship to diet and iron supplementation. Can J Public Health. 1992;83:339-43. | Independent variable
148 | Gokcay,G.,Ozden,T.,Karakas,Z.,Karabayir,N.,Yildiz,I.,Abali,S.,Sahip,Y.. Effect of iron supplementation on development of iron deficiency anemia in breastfed infants. J Trop Pediatr. 2012;58:481-5. | Independent variable
149 | Gondolf,U. H.,Tetens,I.,Michaelsen,K. F.,Trolle,E.. Iron supplementation is positively associated with increased serum ferritin levels in 9-month-old Danish infants. Br J Nutr. 2013;109:103-10. | Study design
150 | Gopaldas,T.,John,C.. Evaluation of a controlled 6 months feeding trial on intake by infants and toddlers fed a high energy-low bulk gruel versus a high energy-high bulk gruel in addition to their habitual home diet. J Trop Pediatr. 1992;38:278-83. | Dependent variable
151 | Gorczyca,D.,Prescha,A.,Szeremeta,K.,Jankowski,A.. Iron status and dietary iron intake of vegetarian children from Poland. Ann Nutr Metab. 2013;62:291-7. | Study design
152 | Graham,E. A.,Carlson,T. H.,Sodergren,K. K.,Detter,J. C.,Labbe,R. F.. Delayed bottle weaning and iron deficiency in southeast Asian toddlers. West J Med. 1997;167:10-4. | Study design, Independent variable
153 | Grant,C. C.,Wall,C. R.,Brunt,D.,Crengle,S.,Scragg,R.. Population prevalence and risk factors for iron deficiency in Auckland, New Zealand. J Paediatr Child Health. 2007;43:532-8. | Study design
154 | Greer,F. R.,Marshall,S.. Bone mineral content, serum vitamin D metabolite concentrations, and ultraviolet B light exposure in infants fed human milk with and without vitamin D2 supplements. J Pediatr. 1989;114:204-12. | Independent variable
155 | Greer,F. R.,Searcy,J. E.,Levin,R. S.,Steichen,J. J.,Steichen-Asche,P. S.,Tsang,R. C.. Bone mineral content and serum 25-hydroxyvitamin D concentrations in breast-fed infants with and without supplemental vitamin D: one-year follow-up. J Pediatr. 1982;100:919-22. | Independent variable
156 | Guerin-Danan,C.,Chabanet,C.,Pedone,C.,Popot,F.,Vaissade,P.,Bouley,C.,Szylit,O.,Andrieux,C.. Milk fermented with yogurt cultures and Lactobacillus casei compared with yogurt and gelled milk: influence on intestinal microflora in healthy infants. Am J Clin Nutr. 1998;67:111-7. | Independent variable
157 | Guldan,G. S.,Fan,H. C.,Ma,X.,Ni,Z. Z.,Xiang,X.,Tang,M. Z.. Culturally appropriate nutrition education improves infant feeding and growth in rural Sichuan, China. J Nutr. 2000;130:1204-11. | Independent variable
158 | Gupta,S.,Venkateswaran,R.,Gorenflo,D. W.,Eyler,A. E.. Childhood iron deficiency anemia, maternal nutritional knowledge, and maternal feeding practices in a high-risk population. Prev Med. 1999;29:152-6. | Study design
159 | Haider,R.,Islam,A.,Kabir,I.,Habte,D.. Early complementary feeding is associated with low nutritional status of young infants recovering from diarrhoea. J Trop Pediatr. 1996;42:170-2. | Health Status
160 | Han,Y. H.,Yon,M.,Han,H. S.,Johnston,K. E.,Tamura,T.,Hyun,T.. Zinc status and growth of Korean infants fed human milk, casein-based, or soy-based formula: three-year longitudinal study. Nutr Res Pract. 2011;5:46-51. | Independent variable
161 | Han,Y. H.,Yon,M.,Han,H. S.,Kim,K. Y.,Tamura,T.,Hyun,T. H.. Folate contents in human milk and casein-based and soya-based formulas, and folate status in Korean infants. Br J Nutr. 2009;101:1769-74. | Independent variable
162 | Hanna,M. D.,Vogelgesang,S. A.,Carroll,N. L.,Murphy,K. K.. Dietary megaloblastic anemia in an infant. S D J Med. 1986;39:7-9. | Study design
163 | Harahap,H.,Jahari,A. B.,Husaini,M. A.,Saco-Pollitt,C.,Pollitt,E.. Effects of an energy and micronutrient supplement on iron deficiency anemia, physical activity and motor and mental development in undernourished children in Indonesia. Eur J Clin Nutr. 2000;54 Suppl 2:S114-9. | Country, Independent variable
164 | Harbild,H. L.,Harslof,L. B.,Christensen,J. H.,Kannass,K. N.,Lauritzen,L.. Fish oil-supplementation from 9 to 12 months of age affects infant attention in a free-play test and is related to change in blood pressure. Prostaglandins Leukot Essent Fatty Acids. 2013;89:327-33. | Independent variable
165 | Harrington,M.,Hotz,C.,Zeder,C.,Polvo,G. O.,Villalpando,S.,Zimmermann,M. B.,Walczyk,T.,Rivera,J. A.,Hurrell,R. F.. A comparison of the bioavailability of ferrous fumarate and ferrous sulfate in non-anemic Mexican women and children consuming a sweetened maize and milk drink. Eur J Clin Nutr. 2011;65:20-5. | Study design, Independent variable
166 | Hasan,J.,Ray,J.,Khan,Z.. Role of weaning in the nutritional status of infant--a longitudinal study in the rural area of Aligarh. J Indian Med Assoc. 1996;94:169, 215. | Study design, Country, Dependent variable
167 | Hay,G.,Clausen,T.,Whitelaw,A.,Trygg,K.,Johnston,C.,Henriksen,T.,Refsum,H.. Maternal folate and cobalamin status predicts vitamin status in newborns and 6-month-old infants. J Nutr. 2010;140:557-64. | Independent variable
168 | Hemalatha,P.,Bhaskaram,P.,Kumar,P. A.,Khan,M. M.,Islam,M. A.. Zinc status of breastfed and formula-fed infants of different gestational ages. J Trop Pediatr. 1997;43:52-4. | Study design, Independent variable
169 | Herman,S.,Griffin,I. J.,Suwarti,S.,Ernawati,F.,Permaesih,D.,Pambudi,D.,Abrams,S. A.. Cofortification of iron-fortified flour with zinc sulfate, but not zinc oxide, decreases iron absorption in Indonesian children. Am J Clin Nutr. 2002;76:813-7. | Country, Independent variable
170 | Ho,M. L.,Yen,H. C.,Tsang,R. C.,Specker,B. L.,Chen,X. C.,Nichols,B. L.. Randomized study of sunshine exposure and serum 25-OHD in breast-fed infants in Beijing, China. J Pediatr. 1985;107:928-31. | Independent variable
171 | Hoffman,D. R.,Birch,E. E.,Birch,D. G.,Uauy,R.,Castaneda,Y. S.,Lapus,M. G.,Wheaton,D. H.. Impact of early dietary intake and blood lipid composition of long-chain polyunsaturated fatty acids on later visual development. J Pediatr Gastroenterol Nutr. 2000;31:540-53. | Independent variable
172 | Hokama,T.. Levels of serum ferritin and total body iron among infants with different feeding regimens. Acta Paediatr Jpn. 1993;35:298-301. | Independent variable
173 | Holmes,S.. Infant feeding. The young vegetarian. Nurs Times. 1987;83:51-5. | Study design
174 | Hop le,T.,Berger,J.. Multiple micronutrient supplementation improves anemia, micronutrient nutrient status, and growth of Vietnamese infants: double-blind, randomized, placebo-controlled trial. J Nutr. 2005;135:660s-665s. | Country, Independent variable
175 | Hopkins,D.,Emmett,P.,Steer,C.,Rogers,I.,Noble,S.,Emond,A.. Infant feeding in the second 6 months of life related to iron status: an observational study. Arch Dis Child. 2007;92:850-4. | Independent variable
176 | Hoyos,C.,Almqvist,C.,Garden,F.,Xuan,W.,Oddy,W. H.,Marks,G. B.,Webb,K. L.. Effect of omega 3 and omega 6 fatty acid intakes from diet and supplements on plasma fatty acid levels in the first 3 years of life. Asia Pac J Clin Nutr. 2008;17:552-7. | Independent variable
177 | Huang,S. C.,Yang,Y. J.,Cheng,C. N.,Chen,J. S.,Lin,C. H.. The etiology and treatment outcome of iron deficiency and iron deficiency anemia in children. J Pediatr Hematol Oncol. 2010;32:282-5. | Study design
178 | Hurrell,R. F.,Reddy,M. B.,Juillerat,M. A.,Cook,J. D.. Degradation of phytic acid in cereal porridges improves iron absorption by human subjects. Am J Clin Nutr. 2003;77:1213-9. | Study design, Age
179 | Hurrell,R. F.. Iron fortification of infant cereals. Bibl Nutr Dieta. 1989:114-22. | Study design
180 | Husaini,M. A.,Jahari,A. B.,Pollitt,E.. The effects of high energy and micronutrient supplementation on iron status in nutritionally at risk infants. Biomed Environ Sci. 1996;9:325-40. | Country, Health Status, Independent variable
181 | Huybregts,L.,Houngbe,F.,Salpeteur,C.,Brown,R.,Roberfroid,D.,Ait-Aissa,M.,Kolsteren,P.. The effect of adding ready-to-use supplementary food to a general food distribution on child nutritional status and morbidity: a cluster-randomized controlled trial. PLoS Med. 2012;9:e1001313. | Country, Independent variable
182 | Innis,S. M.,Nelson,C. M.,Wadsworth,L. D.,MacLaren,I. A.,Lwanga,D.. Incidence of iron-deficiency anaemia and depleted iron stores among nine-month-old infants in Vancouver, Canada. Can J Public Health. 1997;88:80-4. | Study design
183 | Iqbal Hossain,M.,Yasmin,R.,Kabir,I.. Nutritional and immunisation status, weaning practices and socio-economic conditions of under five children in three villages of Bangladesh. Indian J Public Health. 1999;43:37-41. | Study design, Country, Health Status
184 | Isherwood,R. J.,Dimond,C.,Longhurst,S.. Breast feeding and weaning practices in relation to nutritional status of under-5 children in north Bangladesh. J Trop Pediatr. 1988;34:28-31. | Study design, Country
185 | Islam,M. A.,Ahmed,T.,Faruque,A. S.,Rahman,S.,Das,S. K.,Ahmed,D.,Fattori,V.,Clarke,R.,Endtz,H. P.,Cravioto,A.. Microbiological quality of complementary foods and its association with diarrhoeal morbidity and nutritional status of Bangladeshi children. Eur J Clin Nutr. 2012;66:1242-6. | Study design, Dependent variable
186 | Jaber,L.. Preventive intervention for iron deficiency anaemia in a high risk population. Int J Risk Saf Med. 2014;26:155-62. | Independent variable
187 | Jain,V.,Klein,B. P.,Nash,M.,Chapman-Novakofski,K.. Two feasibility studies for introduction of multimicronutrient soy/whey-based supplements in rural homes in Honduras. Journal of Hunger and Environmental Nutrition. 2011;6:247-263. | Country, Independent variable
188 | Jalla,S.,Westcott,J.,Steirn,M.,Miller,L. V.,Bell,M.,Krebs,N. F.. Zinc absorption and exchangeable zinc pool sizes in breast-fed infants fed meat or cereal as first complementary food. J Pediatr Gastroenterol Nutr. 2002;34:35-41. | Dependent variable
189 | James,J.,Evans,J.,Male,P.,Pallister,C.,Hendrikz,J. K.,Oakhill,A.. Iron deficiency in inner city pre-school children: development of a general practice screening programme. J R Coll Gen Pract. 1988;38:250-2. | Study design, Age
190 | Jansen,G.R.,O’B Hourihane. The nutritional status of preschool children in Egypt. World Rev Nutr Diet. 1985;45:42-67. | Study design, Age
191 | Jatanasen,A.,Sacholvicharn,V.,Ongkulna,P.. An evaluation of supplementary feedings of Thai infants in urban slum communities: effect on growth, health and nutritional status. J Med Assoc Thai. 1983;66 Suppl 1:20-9. | Health Status, Dependent variable
192 | Johnson,E. J.,Goyea,H. S.,Ogbeide,M. I.. Nutritional status and weaning patterns of Benin City children. East Afr Med J. 1980;57:405-11. | Country
193 | Jones,K. M.,Ramirez-Zea,M.,Zuleta,C.,Allen,L. H.. Prevalent vitamin B-12 deficiency in twelve-month-old Guatemalan infants is predicted by maternal B-12 deficiency and infant diet. J Nutr. 2007;137:1307-13. | Study design, Independent variable
194 | Kallio,M. J.,Salmenpera,L.,Siimes,M. A.,Perheentupa,J.,Miettinen,T. A.. Exclusive breast-feeding and weaning: effect on serum cholesterol and lipoprotein concentrations in infants during the first year of life. Pediatrics. 1992;89:663-6. | Independent variable, Dependent variable
195 | Karlsson Videhult,F.,Ohlund,I.,Stenlund,H.,Hernell,O.,West,C. E.. Probiotics during weaning: a follow-up study on effects on body composition and metabolic markers at school age. Eur J Nutr. 2015;54:355-63. | Age, Independent variable
196 | Khokhar,A.,Singh,S.,Talwar,R.,Rasania,S. K.,Badhan,S. R.,Mehra,M.. A study of malnutrition among children aged 6 months to 2 years from a resettlement colony of Delhi. Indian J Med Sci. 2003;57:286-9. | Study design, Country, Health Status
197 | Kim,M. J.,Na,B.,No,S. J.,Han,H. S.,Jeong,E. H.,Lee,W.,Han,Y.,Hyeun,T.. Nutritional status of vitamin D and the effect of vitamin D supplementation in Korean breast-fed infants. J Korean Med Sci. 2010;25:83-9. | Independent variable
198 | Kohn,G.,Sawatzki,G.,van Biervliet,J. P.. Long-chain polyunsaturated fatty acids in infant nutrition. Eur J Clin Nutr. 1994;48 Suppl 2:S1-7. | Independent variable
199 | Krebs,N. F. Culbertson D. L. Westcott J. L. Sherlock L. Hambidge K. M.. Normal Iron Status in Breastfed Infants Consuming Meat as an Early Complementary Food. Pediatric Academic Societies Annual Meeting. 2011. | Study design
200 | Krebs,N. F.,Hambidge,K. M.,Mazariegos,M.,Westcott,J.,Goco,N.,Wright,L. L.,Koso-Thomas,M.,Tshefu,A.,Bose,C.,Pasha,O.,Goldenberg,R.,Chomba,E.,Carlo,W.,Kindem,M.,Das,A.,Hartwell,T.,McClure,E.. Complementary feeding: a Global Network cluster randomized controlled trial. BMC Pediatr. 2011;11:4. | Study design, Country
201 | Krebs,N. F.,Hambidge,K. M.,Westcott,J. E.,Miller,L. V.,Sian,L.,Bell,M.,Grunwald,G.. Exchangeable zinc pool size in infants is related to key variables of zinc homeostasis. J Nutr. 2003;133:1498s-501s. | Dependent variable
202 | Krebs,N. F.,Mazariegos,M.,Chomba,E.,Sami,N.,Pasha,O.,Tshefu,A.,Carlo,W. A.,Goldenberg,R. L.,Bose,C. L.,Wright,L. L.,Koso-Thomas,M.,Goco,N.,Kindem,M.,McClure,E. M.,Westcott,J.,Garces,A.,Lokangaka,A.,Manasyan,A.,Imenda,E.,Hartwell,T. D.,Hambidge,K. M.. Randomized controlled trial of meat compared with multimicronutrient-fortified cereal in infants and toddlers with high stunting rates in diverse settings. Am J Clin Nutr. 2012;96:840-7. | Country
203 | Krebs,N. F.,Reidinger,C. J.,Robertson,A. D.,Hambidge,K. M.. Growth and intakes of energy and zinc in infants fed human milk. J Pediatr. 1994;124:32-9. | Dependent variable
204 | Kreiter,S. R.,Schwartz,R. P.,Kirkman,H. N.,Jr.,Charlton,P. A.,Calikoglu,A. S.,Davenport,M. L.. Nutritional rickets in African American breast-fed infants. J Pediatr. 2000;137:153-7. | Study design, Health Status
205 | Kuipers,R. S.,Luxwolda,M. F.,Sango,W. S.,Kwesigabo,G.,Dijck-Brouwer,D. A.,Muskiet,F. A.. Postdelivery changes in maternal and infant erythrocyte fatty acids in 3 populations differing in fresh water fish intakes. Prostaglandins Leukot Essent Fatty Acids. 2011;85:387-97. | Independent variable
206 | Ladhani,S.,Srinivasan,L.,Buchanan,C.,Allgrove,J.. Presentation of vitamin D deficiency. Arch Dis Child. 2004;89:781-4. | Study design, Health Status, Independent variable
207 | Lampe,J. B.,Velez,N.. The effect of prolonged bottle feeding on cow’s milk intake and iron stores at 18 months of age. Clin Pediatr (Phila). 1997;36:569-72. | Independent variable, Dependent variable
208 | Lande,B.,Andersen,L. F.,Baerug,A.,Trygg,K. U.,Lund-Larsen,K.,Veierod,M. B.,Bjorneboe,G. E.. Infant feeding practices and associated factors in the first six months of life: the Norwegian infant nutrition survey. Acta Paediatr. 2003;92:152-61. | Study design, Dependent variable
209 | Lartey,A.,Manu,A.,Brown,K. H.,Dewey,K. G.. Predictors of micronutrient status among six- to twelve-month-old breast-fed Ghanaian infants. J Nutr. 2000;130:199-207. | Country
210 | Lartey,A.,Manu,A.,Brown,K. H.,Peerson,J. M.,Dewey,K. G.. A randomized, community-based trial of the effects of improved, centrally processed complementary foods on growth and micronutrient status of Ghanaian infants from 6 to 12 mo of age. Am J Clin Nutr. 1999;70:391-404. | Country
211 | Lartey,A.,Manu,A.,Brown,K. H.,Peerson,J. M.,Dewey,K. G.. Predictors of growth from 1 to 18 months among breast-fed Ghanaian infants. Eur J Clin Nutr. 2000;54:41-9. | Country
212 | Lauritzen,L.,Hoppe,C.,Straarup,E. M.,Michaelsen,K. F.. Maternal fish oil supplementation in lactation and growth during the first 2.5 years of life. Pediatr Res. 2005;58:235-42. | Independent variable
213 | Lavon,B.,Tulchinsky,T. H.,Preger,M.,Said,R.,Kaufman,S.. Iron deficiency anemia among Jewish and Arab infants at 6 and 12 months of age in Hadera, Israel. Isr J Med Sci. 1985;21:107-12. | Study design, Independent variable
214 | Lehmann,F.,Gray-Donald,K.,Mongeon,M.,Di Tommaso,S.. Iron deficiency anemia in 1-year-old children of disadvantaged families in Montreal. Cmaj. 1992;146:1571-7. | Study design
215 | Lehtonen,E.,Ormisson,A.,Nucci,A.,Cuthbertson,D.,Sorkio,S.,Hyytinen,M.,Alahuhta,K.,Berseth,C.,Salonen,M.,Taback,S., Franciscus,M.,Gonzalez-Frutos,T.,Korhonen,T. E.,Lawson,M. L.,Becker,D. J.,Krischer,J. P.,Knip,M.,Virtanen,S. M.. Use of vitamin D supplements during infancy in an international feeding trial. Public Health Nutr. 2014;17:810-22. | Independent variable, Dependent variable
216 | Leung,S. S.,Davies,D. P.,Lui,S.,Lo,L.,Yuen,P.,Swaminathan,R.,Hom,B. L.. Iron status of Hong Kong babies at 18 months. J Singapore Paediatr Soc. 1987;29 Suppl 1:108-12. | Independent variable, Dependent variable
217 | Leung,S. S.,Lui,S.,Swaminathan,R.. Vitamin D status of Hong Kong Chinese infants. Acta Paediatr Scand. 1989;78:303-6. | Study design, Independent variable
218 | Lind,T.,Persson,L.,Lonnerdal,B.,Stenlund,H.,Hernell,O.. Effects of weaning cereals with different phytate content on growth, development and morbidity: a randomized intervention trial in infants from 6 to 12 months of age. Acta Paediatr. 2004;93:1575-82. | Dependent variable
219 | Lioret,S.,McNaughton,S. A.,Spence,A. C.,Crawford,D.,Campbell,K. J.. Tracking of dietary intakes in early childhood: the Melbourne InFANT Program. Eur J Clin Nutr. 2013;67:275-81. | Dependent variable
220 | Lönnerdal,B.,Hernell,O.. Under and over nutrition of iron in infancy and early childhood. Pakistan Paediatric Journal. 2014;38:132-133. | Study design
221 | Lopez de Romana,G.,Cusirramos,S.,Lopez de Romana,D.,Gross,R.. Efficacy of multiple micronutrient supplementation for improving anemia, micronutrient status, growth, and morbidity of Peruvian infants. J Nutr. 2005;135:646s-652s. | Independent variable
222 | Lozoff,B.,De Andraca,I.,Castillo,M.,Smith,J. B.,Walter,T.,Pino,P.. Behavioral and developmental effects of preventing iron-deficiency anemia in healthy full-term infants. Pediatrics. 2003;112:846-54. | Independent variable
223 | Lozoff,B.,Kaciroti,N.,Walter,T.. Iron deficiency in infancy: applying a physiologic framework for prediction. Am J Clin Nutr. 2006;84:1412-21. | Independent variable
224 | Lundeen,E.,Schueth,T.,Toktobaev,N.,Zlotkin,S.,Hyder,S. M.,Houser,R.. Daily use of Sprinkles micronutrient powder for 2 months reduces anemia among children 6 to 36 months of age in the Kyrgyz Republic: a cluster-randomized trial. Food Nutr Bull. 2010;31:446-60. | Country, Independent variable
225 | Lutter,C. K.,Rodriguez,A.,Fuenmayor,G.,Avila,L.,Sempertegui,F.,Escobar,J.. Growth and micronutrient status in children receiving a fortified complementary food. J Nutr. 2008;138:379-88. | Independent variable
226 | Luukkainen,P.,Salo,M. K.,Visakorpi,J. K.,Raiha,N. C.,Nikkari,T.. Impact of solid food on plasma arachidonic and docosahexaenoic acid status of term infants at 8 months of age. J Pediatr Gastroenterol Nutr. 1996;23:229-34. | Independent variable
227 | Luxwolda,M. F.,Kuipers,R. S.,Boersma,E. R.,van Goor,S. A.,Dijck-Brouwer,D. A.,Bos,A. F.,Muskiet,F. A.. DHA status is positively related to motor development in breastfed African and Dutch infants. Nutr Neurosci. 2014;17:97-103. | Country
228 | Majid Molla,A.,Badawi,M. H.,al-Yaish,S.,Sharma,P.,el-Salam,R. S.,Molla,A. M.. Risk factors for nutritional rickets among children in Kuwait. Pediatr Int. 2000;42:280-4. | Dependent variable
229 | Makrides,M.,Gould,J. F.,Gawlik,N. R.,Yelland,L. N.,Smithers,L. G.,Anderson,P. J.,Gibson,R. A.. Four-year follow-up of children born to women in a randomized trial of prenatal DHA supplementation. Jama. 2014;311:1802-4. | Independent variable
230 | Mamabolo,R. L.,Alberts,M.,Levitt,N. S.,Delemarre-van de Waal,H. A.,Steyn,N. P.. Association between insulin-like growth factor-1, insulin-like growth factor-binding protein-1 and leptin levels with nutritional status in 1-3-year-old children, residing in the central region of Limpopo Province, South Africa. Br J Nutr. 2007;98:762-9. | Age, Country, Independent variable
231 | Martínez Andrade,G. O.,Duque-López,M. X.,Cruz-González,M. B.,Martínez-Salgado,H.. The efect of diverse interventionist nutritional strategies aimed at diminishing anemia frequency and iron deficiency among childeren at Mexican Institute of Indigineous affairs boarding schools in the state of Hidalgo. Saludarte. 2001;2:7-21. | Age, Language
232 | Martinez,C.,Fox,T.,Eagles,J.,Fairweather-Tait,S.. Evaluation of iron bioavailability in infant weaning foods fortified with haem concentrate. J Pediatr Gastroenterol Nutr. 1998;27:419-24. | Dependent variable
233 | Matsuo,K.,Mukai,T.,Suzuki,S.,Fujieda,K.. Prevalence and risk factors of vitamin D deficiency rickets in Hokkaido, Japan. Pediatr Int. 2009;51:559-62. | Study design
234 | Mazariegos,M.,Hambidge,K. M.,Westcott,J. E.,Solomons,N. W.,Raboy,V.,Das,A.,Goco,N.,Kindem,M.,Wright,L. L.,Krebs,N. F.. Neither a zinc supplement nor phytate-reduced maize nor their combination enhance growth of 6- to 12-month-old Guatemalan infants. J Nutr. 2010;140:1041-8. | Country, Independent variable
235 | McAllister,J. C.,Lane,A. T.,Buckingham,B. A.. Vitamin D deficiency in the San Francisco Bay Area. J Pediatr Endocrinol Metab. 2006;19:205-8. | Study design
236 | Meldrum,S. J.,D’Vaz,N.,Casadio,Y.,Dunstan,J. A.,Niels Krogsgaard-Larsen,N.,Simmer,K.,Prescott,S. L.. Determinants of DHA levels in early infancy: differential effects of breast milk and direct fish oil supplementation. Prostaglandins Leukot Essent Fatty Acids. 2012;86:233-9. | Independent variable
237 | Meldrum,S. J.,D’Vaz,N.,Simmer,K.,Dunstan,J. A.,Hird,K.,Prescott,S. L.. Effects of high-dose fish oil supplementation during early infancy on neurodevelopment and language: a randomised controlled trial. Br J Nutr. 2012;108:1443-54. | Independent variable, Dependent variable
238 | Menon,P.,Bamezai,A.,Subandoro,A.,Ayoya,M. A.,Aguayo,V.. Age-appropriate infant and young child feeding practices are associated with child nutrition in India: insights from nationally representative data. Matern Child Nutr. 2015;11:73-87. | Study design, Country
239 | Merewood,A.,Mehta,S. D.,Grossman,X.,Chen,T. C.,Mathieu,J.,Holick,M. F.,Bauchner,H.. Vitamin D status among 4-month-old infants in New England: a prospective cohort study. J Hum Lact. 2012;28:159-66. | Independent variable
240 | Merhav,H.,Amitai,Y.,Palti,H.,Godfrey,S.. Tea drinking and microcytic anemia in infants. Am J Clin Nutr. 1985;41:1210-3. | Study design, Independent variable
241 | Michaelsen,K. F.. Cows’ milk in complementary feeding. Pediatrics. 2000;106:1302-3. | Study design
242 | Michaelsen,K. F.. Nutrition and growth during infancy. The Copenhagen Cohort Study. Acta Paediatr Suppl. 1997;420:1-36. | Study design
243 | Milankov,O.,Bjelica,M.,Savic,R.. What kind of milk can prevent infant’s sideropenic anemia--comparative study. Med Pregl. 2014;67:167-71. | Study design, Health Status
244 | Mira,M.,Alperstein,G.,Karr,M.,Ranmuthugala,G.,Causer,J.,Niec,A.,Lilburne,A. M.. Haem iron intake in 12-36 month old children depleted in iron: case-control study. Bmj. 1996;312:881-3. | Independent variable
245 | Mize,C. E.,Uauy,R.,Kramer,R.,Benser,M.,Allen,S.,Grundy,S. M.. Lipoprotein-cholesterol responses in healthy infants fed defined diets from ages 1 to 12 months: comparison of diets predominant in oleic acid versus linoleic acid, with parallel observations in infants fed a human milk-based diet. J Lipid Res. 1995;36:1178-87. | Independent variable, Dependent variable
246 | Monajemzadeh,S. M.,Zarkesh,M. R.. Iron deficiency anemia in infants aged 12-15 months in Ahwaz, Iran. Indian J Pathol Microbiol. 2009;52:182-4. | Study design
247 | Montalto,M. B.,Benson,J. D.,Martinez,G. A.. Nutrient intakes of formula-fed infants and infants fed cow’s milk. Pediatrics. 1985;75:343-51. | Study design
248 | Monterrosa,E. C.,Frongillo,E. A.,Vasquez-Garibay,E. M.,Romero-Velarde,E.,Casey,L. M.,Willows,N. D.. Predominant breast-feeding from birth to six months is associated with fewer gastrointestinal infections and increased risk for iron deficiency among infants. J Nutr. 2008;138:1499-504. | Independent variable
249 | Morgan,J.,Taylor,A.,Fewtrell,M.. Meat consumption is positively associated with psychomotor outcome in children up to 24 months of age. J Pediatr Gastroenterol Nutr. 2004;39:493-8. | Dependent variable
250 | Morin,K. H.. Update on what and how much infants and toddlers eat. MCN Am J Matern Child Nurs. 2006;31:269. | Study design
251 | Morley,R.,Abbott,R.,Fairweather-Tait,S.,MacFadyen,U.,Stephenson,T.,Lucas,A.. Iron fortified follow on formula from 9 to 18 months improves iron status but not development or growth: a randomised trial. Arch Dis Child. 1999;81:247-52. | Independent variable
252 | Mostert,D.,Steyn,N. P.,Temple,N. J.,Olwagen,R.. Dietary intake of pregnant women and their infants in a poor black South African community. Curationis. 2005;28:12-9. | Country, Dependent variable
253 | Moussalem,M.. Iron deficiency in newborns and infant. Revue Medicale Libanaise. 1999;11:12-16. | Language
254 | Mughal,M. Z.,Salama,H.,Greenaway,T.,Laing,I.,Mawer,E. B.. Lesson of the week: florid rickets associated with prolonged breast feeding without vitamin D supplementation. Bmj. 1999;318:39-40. | Study design
255 | Murphy,E.,Collins,M.,Gill,D.,Shortt,H.. Iron and nutritional status of toddlers. Ir Med J. 1992;85:33-4. | Study design, Age
256 | Mushaphi,L. F.,Mbhenyane,X. G.,Khoza,L. B.,Amey,A. K. A.. Infant-feeding practices of mothers and the nutritional status of infants in the Vhembe District of Limpopo Province. South African Journal of Clinical Nutrition. 2008;21:36-41. | Study design, Country
257 | Nagpal,J.,Sachdev,H. P.,Singh,T.,Mallika,V.. A randomized placebo-controlled trial of iron supplementation in breastfed young infants initiated on complementary feeding: effect on haematological status. J Health Popul Nutr. 2004;22:203-11. | Country, Independent variable
258 | Navarro,J. I.,Sigulem,D. M.,Ferraro,A. A.,Polanco,J. J.,Barros,A. J.. The double task of preventing malnutrition and overweight: a quasi-experimental community-based trial. BMC Public Health. 2013;13:212. | Independent variable, Dependent variable
259 | Nnanyelugo,D. O.. Nutritional practices and food intake measurements and their relationship to socio-economic grouping, location and their apparent nutritional adequacy in children. Appetite. 1982;3:229-41. | Study design, Country
260 | Norgate,C.. Best practice in weaning. Nurs Times. 2001;97:56-7. | Study design
261 | Ntouva,A.,Rogers,I.,MacAdam,A.,Emmett,P.. Weaning practices and iron status of exclusively breast fed infants. Journal of Human Nutrition & Dietetics. 2011;24:297-298 2p. | Study design
262 | Nube,M.,Asenso-Okyere,W. K.. Large differences in nutritional status between fully weaned and partially breast fed children beyond the age of 12 months. Eur J Clin Nutr. 1996;50:171-7. | Study design, Country
263 | Obatolu,V. A.. Growth pattern of infants fed with a mixture of extruded malted maize and cowpea. Nutrition. 2003;19:174-8. | Country, Independent variable
264 | O’Donovan,S. M.,Murray,D. M.,Hourihane,J. O.,Kenny,L. C.,Irvine,A. D.,Kiely,M.. Cohort profile: The Cork BASELINE Birth Cohort Study: Babies after SCOPE: Evaluating the Longitudinal Impact on Neurological and Nutritional Endpoints. Int J Epidemiol. 2015;44:764-75. | Study design, Dependent variable
265 | Oelofse,A.,Van Raaij,J. M.,Benade,A. J.,Dhansay,M. A.,Tolboom,J. J.,Hautvast,J. G.. The effect of a micronutrient-fortified complementary food on micronutrient status, growth and development of 6- to 12-month-old disadvantaged urban South African infants. Int J Food Sci Nutr. 2003;54:399-407. | Country
266 | Oien,T.,Storro,O.,Johnsen,R.. Do early intake of fish and fish oil protect against eczema and doctor-diagnosed asthma at 2 years of age? A cohort study. J Epidemiol Community Health. 2010;64:124-9. | Dependent variable
267 | Olmedo,S. I.,Valeggia,C.. The initiation of complementary feeding among Qom indigenous people. Arch Argent Pediatr. 2014;112:254-7. | Study design, Dependent variable
268 | Osorio,M. M.,Lira,P. I.,Ashworth,A.. Factors associated with Hb concentration in children aged 6-59 months in the State of Pernambuco, Brazil. Br J Nutr. 2004;91:307-15. | Study design
269 | Owino,V. O.,Kasonka,L. M.,Sinkala,M. M.,Wells,J. K.,Eaton,S.,Darch,T.,Coward,A.,Tomkins,A. M.,Filteau,S. M.. Fortified complementary foods with or without alpha-amylase treatment increase hemoglobin but do not reduce breast milk intake of 9-mo-old Zambian infants. Am J Clin Nutr. 2007;86:1094-103. | Study design, Country, Independent variable
270 | Palti,H.. Anemia in infancy. Public Health Rev. 2000;28:89-92. | Study design
271 | Paredes-Rojas,R. R.,Solomons,H. C.. Food for thought: impact of a supplemental nutritional program on low-income preschool children. Pediatr Nurs. 1982;8:315-7. | Age
272 | Park,J. S.,Chang,J. Y.,Hong,J.,Ko,J. S.,Seo,J. K.,Shin,S.,Lee,E. H.. Nutritional zinc status in weaning infants: association with iron deficiency, age, and growth profile. Biol Trace Elem Res. 2012;150:91-102. | Study design
273 | Pastel,R. A.,Howanitz,P. J.,Oski,F. A.. Iron sufficiency with prolonged exclusive breast-feeding in Peruvian infants. Clin Pediatr (Phila). 1981;20:625-6. | Study design
274 | Peng,L. F.,Serwint,J. R.. A comparison of breastfed children with nutritional rickets who present during and after the first year of life. Clin Pediatr (Phila). 2003;42:711-7. | Study design
275 | Persson,L. A.,Lundstrom,M.,Lonnerdal,B.,Hernell,O.. Are weaning foods causing impaired iron and zinc status in 1-year-old Swedish infants? A cohort study. Acta Paediatr. 1998;87:618-22. | Study design, Independent variable
276 | Phu,P. V.,Hoan,N. V.,Salvignol,B.,Treche,S.,Wieringa,F. T.,Khan,N. C.,Tuong,P. D.,Berger,J.. Complementary foods fortified with micronutrients prevent iron deficiency and anemia in Vietnamese infants. J Nutr. 2010;140:2241-7. | Country
277 | Pizarro,F.,Yip,R.,Dallman,P. R.,Olivares,M.,Hertrampf,E.,Walter,T.. Iron status with different infant feeding regimens: relevance to screening and prevention of iron deficiency. J Pediatr. 1991;118:687-92. | Study design
278 | Pludowski,P.,Socha,P.,Karczmarewicz,E.,Zagorecka,E.,Lukaszkiewicz,J.,Stolarczyk,A.,Piotrowska-Jastrzebska,J.,Kryskiewicz,E.,Lorenc,R. S.,Socha,J.. Vitamin D supplementation and status in infants: a prospective cohort observational study. J Pediatr Gastroenterol Nutr. 2011;53:93-9. | Independent variable
279 | Poh,Bee Koon,Ng,Boon Koon,Siti Haslinda,Mohd Din,Nik Shanita,Safii,Wong,Jyh Eiin,Budin,Siti Balkis,Ruzita,Abd Talib,Ng,Lai Oon,Khouw,Ilse,Norimah,A. Karim. Nutritional status and dietary intakes of children aged 6 months to 12 years: findings of the Nutrition Survey of Malaysian Children (SEANUTS Malaysia). British Journal of Nutrition. 2013;110:S21-35 1p. | Study design
280 | Polat,T. B.,Saz,E. U.,Urganci,N.,Akyildiz,B.,Celmeli,F.. Evaluation of iron status in relation to feeding practices in early infancy. Macedonian Journal of Medical Sciences. 2011;4:70-74. | Independent variable
281 | Pollitt,E.,Watkins,W. E.,Husaini,M. A.. Three-month nutritional supplementation in Indonesian infants and toddlers benefits memory function 8 y later. Am J Clin Nutr. 1997;66:1357-63. | Country, Dependent variable
282 | Radhakrishna,K. V.,Hemalatha,R.,Geddam,J. J.,Kumar,P. A.,Balakrishna,N.,Shatrugna,V.. Effectiveness of zinc supplementation to full term normal infants: a community based double blind, randomized, controlled, clinical trial. PLoS One. 2013;8:e61486. | Independent variable
283 | Rah,J. H.,Akhter,N.,Semba,R. D.,de Pee,S.,Bloem,M. W.,Campbell,A. A.,Moench-Pfanner,R.,Sun,K.,Badham,J.,Kraemer,K.. Low dietary diversity is a predictor of child stunting in rural Bangladesh. Eur J Clin Nutr. 2010;64:1393-8. | Study design, Country, Dependent variable
284 | Rannan-Eliya,R. P.,Hossain,S. M.,Anuranga,C.,Wickramasinghe,R.,Jayatissa,R.,Abeykoon,A. T.. Trends and determinants of childhood stunting and underweight in Sri Lanka. Ceylon Med J. 2013;58:10-8. | Study design
285 | Rao,S.,Rajpathak,V.. Breastfeeding and weaning practices in relation to nutritional status of infants. Indian Pediatr. 1992;29:1533-9. | Study design, Independent variable, Dependent variable
286 | Reghu,A.,Hosdurga,S.,Sandhu,B.,Spray,C.. Vitamin B12 deficiency presenting as oedema in infants of vegetarian mothers. Eur J Pediatr. 2005;164:257-8. | Study design
287 | Requejo,A. M.,Navia,B.,Ortega,R. M.,Lopez-Sobaler,A. M.,Quintas,E.,Gaspar,M. J.,Osorio,O.. The age at which meat is first included in the diet affects the incidence of iron deficiency and ferropenic anaemia in a group of pre-school children from Madrid. Int J Vitam Nutr Res. 1999;69:127-31. | Age
288 | Reurings,M.,Vossenaar,M.,Doak,C. M.,Solomons,N. W.. Stunting rates in infants and toddlers born in metropolitan Quetzaltenango, Guatemala. Nutrition. 2013;29:655-60. | Study design, Health Status, Dependent variable
289 | Rim,H.,Kim,S.,Sim,B.,Gang,H.,Kim,H.,Kim,Y.,Kim,R.,Yang,M.,Kim,S.. Effect of iron fortification of nursery complementary food on iron status of infants in the DPRKorea. Asia Pac J Clin Nutr. 2008;17:264-9. | Country
290 | Rivera,J. A.,Habicht,J. P.. Effect of supplementary feeding on the prevention of mild-to-moderate wasting in conditions of endemic malnutrition in Guatemala. Bull World Health Organ. 2002;80:926-32. | Country, Health Status, Independent variable, Dependent variable
291 | Rivera,J. A.,Ruel,M. T.,Santizo,M. C.,Lonnerdal,B.,Brown,K. H.. Zinc supplementation improves the growth of stunted rural Guatemalan infants. J Nutr. 1998;128:556-62. | Country, Health Status
292 | Roche,M. L.,Creed-Kanashiro,H. M.,Tuesta,I.,Kuhnlein,H. V.. Infant and young child feeding in the Peruvian Amazon: the need to promote exclusive breastfeeding and nutrient-dense traditional complementary foods. Matern Child Nutr. 2011;7:284-94. | Study design, Dependent variable
293 | Rojroongwasinkul,Nipa,Kijboonchoo,Kallaya,Wimonpeerapattana,Wanphen,Purttiponthanee,Sasiumphai,Yamborisut,Ur uwan,Boonpraderm,Atitada,Kunapan,Petcharat,Thasanasuwan,Wiyada,Khouw,Ilse. SEANUTS: the nutritional status and dietary intakes of 0.5–12-year-old Thai children. British Journal of Nutrition. 2013;110:S36-44 1p. | Study design
294 | Rosado,J. L.,Lopez,P.,Garcia,O. P.,Alatorre,J.,Alvarado,C.. Effectiveness of the nutritional supplement used in the Mexican Oportunidades programme on growth, anaemia, morbidity and cognitive development in children aged 12-24 months. Public Health Nutr. 2011;14:931-7. | Health Status, Independent variable, Dependent variable
295 | Roy,S. K.,Jolly,S. P.,Shafique,S.,Fuchs,G. J.,Mahmud,Z.,Chakraborty,B.,Roy,S.. Prevention of malnutrition among young children in rural Bangladesh by a food-health-care educational intervention: a randomized, controlled trial. Food Nutr Bull. 2007;28:375-83. | Country, Independent variable
296 | Ryan,A. S.,Martinez,G. A.,Krieger,F. W.. Feeding low-fat milk during infancy. Am J Phys Anthropol. 1987;73:539-48. | Independent variable, Dependent variable, Language
297 | Sadowitz,P. D.,Oski,F. A.. Iron status and infant feeding practices in an urban ambulatory center. Pediatrics. 1983;72:33-6. | Study design
298 | Salo,P.,Viikari,J.,Hamalainen,M.,Lapinleimu,H.,Routi,T.,Ronnemaa,T.,Seppanen,R.,Jokinen,E.,Valimaki,I.,Simell,O.. Serum cholesterol ester fatty acids in 7- and 13-month-old children in a prospective randomized trial of a low-saturated fat, low-cholesterol diet: the STRIP baby project. Special Turku coronary Risk factor Intervention Project for children. Acta Paediatr. 1999;88:505-12. | Independent variable
299 | Salvioli,G. P.,Faldella,G.,Alessandroni,R.,Lanari,M.,Di Turi,R. P.. Iron nutrition and iron status changes in Italian infants in the last decade. Ann Ist Super Sanita. 1995;31:455-9. | Study design, Independent variable
300 | Samadpour,K.,Long,K. Z.,Hayatbakhsh,R.,Marks,G. C.. Randomised comparison of the effects of Sprinkles and Foodlets with the currently recommended supplement (Drops) on micronutrient status and growth in Iranian children. Eur J Clin Nutr. 2011;65:1287-94. | Independent variable
301 | Sant’Ana,L. F. D. R.,Cruz,A. C. R. F. D.,Franceschini,S. D. C. C.,Costa,N. M. B.. Effect of a multi-mixture in the nutritional status of preschool children regarding iron. Revista de Nutricao. 2006;19:445-454. | Age
302 | Sazawal,S.,Dhingra,P.,Dhingra,U.,Gupta,S.,Iyengar,V.,Menon,V. P.,Sarkar,A.,Black,R. E.. Compliance with home-based fortification strategies for delivery of iron and zinc: its effect on haematological and growth markers among 6-24 months old children in north India. J Health Popul Nutr. 2014;32:217-26. | Country
303 | Sazawal,S.,Dhingra,U.,Dhingra,P.,Hiremath,G.,Sarkar,A.,Dutta,A.,Menon,V. P.,Black,R. E.. Micronutrient fortified milk improves iron status, anemia and growth among children 1-4 years: a double masked, randomized, controlled trial. PLoS One. 2010;5:e12167. | Age
304 | Scatliff,C. E.,Koski,K. G.,Scott,M. E.. Diarrhea and novel dietary factors emerge as predictors of serum vitamin B12 in Panamanian children. Food Nutr Bull. 2011;32:54-9. | Age
305 | Schmidt,M. K.,Muslimatun,S.,West,C. E.,Schultink,W.,Gross,R.,Hautvast,J. G.. Nutritional status and linear growth of Indonesian infants in west java are determined more by prenatal environment than by postnatal factors. J Nutr. 2002;132:2202-7. | Country, Health Status, Dependent variable
306 | Seal,A.,Kafwembe,E.,Kassim,I. A.,Hong,M.,Wesley,A.,Wood,J.,Abdalla,F.,van den Briel,T.. Maize meal fortification is associated with improved vitamin A and iron status in adolescents and reduced childhood anaemia in a food aid-dependent refugee population. Public Health Nutr. 2008;11:720-8. | Study design, Health Status
307 | Shaikh,U.,Alpert,P. T.. Nutritional rickets in Las Vegas, Nevada. J Pediatr Endocrinol Metab. 2006;19:209-12. | Study design
308 | Shamah-Levy,T.,Villalpando,S.,Rivera-Dommarco,J. A.,Mundo-Rosas,V.,Cuevas-Nasu,L.,Jimenez-Aguilar,A.. Ferrous gluconate and ferrous sulfate added to a complementary food distributed by the Mexican nutrition program Oportunidades have a comparable efficacy to reduce iron deficiency in toddlers. J Pediatr Gastroenterol Nutr. 2008;47:660-6. | Independent variable
309 | Sheng,X.,Tong,M.,Zhao,D.,Leung,T. F.,Zhang,F.,Hays,N. P.,Ge,J.,Ho,W. M.,Northington,R.,Terry,D. L.,Yao,M.. Randomized controlled trial to compare growth parameters and nutrient adequacy in children with picky eating behaviors who received nutritional counseling with or without an oral nutritional supplement. Nutr Metab Insights. 2014;7:85-94. | Age, Independent variable
310 | Shi,L.,Zhang,J.,Wang,Y.,Caulfield,L. E.,Guyer,B.. Effectiveness of an educational intervention on complementary feeding practices and growth in rural China: a cluster randomised controlled trial. Public Health Nutr. 2010;13:556-65. | Independent variable
311 | Siega-Riz,A. M.,Estrada Del Campo,Y.,Kinlaw,A.,Reinhart,G. A.,Allen,L. H.,Shahab-Ferdows,S.,Heck,J.,Suchindran,C. M.,Bentley,M. E.. Effect of supplementation with a lipid-based nutrient supplement on the micronutrient status of children aged 6-18 months living in the rural region of Intibuca, Honduras. Paediatr Perinat Epidemiol. 2014;28:245-54. | Health Status, Independent variable
312 | Siimes,M. A.,Salmenpera,L.,Perheentupa,J.. Exclusive breast-feeding for 9 months: risk of iron deficiency. J Pediatr. 1984;104:196-9. | Independent variable
313 | Silva,A. P.,Vitolo,M. R.,Zara,L. F.,Castro,C. F.. Effects of zinc supplementation on 1- to 5-year old children. J Pediatr (Rio J). 2006;82:227-31. | Independent variable, Language
314 | Simoes,E. A.,Pereira,S. M.. The growth of exclusively breastfed infants. Ann Trop Paediatr. 1986;6:17-21. | Dependent variable
315 | Siti-Noor,A. S.,Wan-Maziah,W. M.,Narazah,M. Y.,Quah,B. S.. Prevalence and risk factors for iron deficiency in Kelantanese pre-school children. Singapore Med J. 2006;47:935-9. | Study design
316 | Skau,J. K.,Touch,B.,Chhoun,C.,Chea,M.,Unni,U. S.,Makurat,J.,Filteau,S.,Wieringa,F. T.,Dijkhuizen,M. A.,Ritz,C.,Wells,J. C.,Berger,J.,Friis,H.,Michaelsen,K. F.,Roos,N.. Effects of animal source food and micronutrient fortification in complementary food products on body composition, iron status, and linear growth: a randomized trial in Cambodia. Am J Clin Nutr. 2015;101:742-51. | Country
317 | Skinner,J. D.,Carruth,B. R.,Houck,K. S.,Coletta,F.,Cotter,R.,Ott,D.,McLeod,M.. Longitudinal study of nutrient and food intakes of infants aged 2 to 24 months. J Am Diet Assoc. 1997;97:496-504. | Dependent variable
318 | Smith,A. M.,Picciano,M. F.,Deering,R. H.. Folate intake and blood concentrations of term infants. Am J Clin Nutr. 1985;41:590-8. | Independent variable
319 | Smithers,L. G.,Golley,R. K.,Brazionis,L.,Emmett,P.,Northstone,K.,Lynch,J. W.. Dietary patterns of infants and toddlers are associated with nutrient intakes. Nutrients. 2012;4:935-48. | Dependent variable
320 | Smuts,C. M.,Lombard,C. J.,Benade,A. J.,Dhansay,M. A.,Berger,J.,Hop le,T.,Lopez de Romana,G.,Untoro,J.,Karyadi,E.,Erhardt,J.,Gross,R.. Efficacy of a foodlet-based multiple micronutrient supplement for preventing growth faltering, anemia, and micronutrient deficiency of infants: the four country IRIS trial pooled data analysis. J Nutr. 2005;135:631s-638s. | Study design, Independent variable
321 | Souganidis,E. S.,Sun,K.,de Pee,S.,Kraemer,K.,Rah,J. H.,Moench-Pfanner,R.,Sari,M.,Bloem,M. W.,Semba,R. D.. Determinants of anemia clustering among mothers and children in Indonesia. J Trop Pediatr. 2012;58:170-7. | Study design, Independent variable
322 | Specker,B. L.,Ho,M. L.,Oestreich,A.,Yin,T. A.,Shui,Q. M.,Chen,X. C.,Tsang,R. C.. Prospective study of vitamin D supplementation and rickets in China. J Pediatr. 1992;120:733-9. | Study design, Independent variable
323 | Sreedhara,M. S.,Banapurmath,C. R.. A study of nutritional status of infants in relation to their complementary feeding practices. Current Pediatric Research. 2014;18:39-41. | Study design
324 | Stang,J.. Improving the eating patterns of infants and toddlers. J Am Diet Assoc. 2006;106:S7-9. | Study design
325 | Stekel,A.,Olivares,M.,Cayazzo,M.,Chadud,P.,Llaguno,S.,Pizarro,F.. Prevention of iron deficiency by milk fortification. II. A field trial with a full-fat acidified milk. Am J Clin Nutr. 1988;47:265-9. | Age, Independent variable
326 | Sultan,A. N.,Zuberi,R. W.. Late weaning: the most significant risk factor in the development of iron deficiency anaemia at 1-2 years of age. J Ayub Med Coll Abbottabad. 2003;15:3-7. | Country
327 | Tang,M.,Sheng,X. Y.,Krebs,N. F.,Hambidge,K. M.. Meat as complementary food for older breastfed infants and toddlers: a randomized, controlled trial in rural China. Food Nutr Bull. 2014;35:S188-92. | Dependent variable
328 | Thakwalakwa,C. M.,Ashorn,P.,Phuka,J. C.,Cheung,Y. B.,Briend,A.,Maleta,K. M.. Impact of lipid-based nutrient supplements and corn-soy blend on energy and nutrient intake among moderately underweight 8-18-month-old children participating in a clinical trial. Matern Child Nutr. 2014. | Independent variable, Dependent variable
329 | Thorsdottir,I.,Gunnarsson,B. S.. Dietary quality and adequacy of micronutrient intakes in children. Proc Nutr Soc. 2006;65:366-75. | Study design
330 | Torrejon,C. S.,Castillo-Duran,C.,Hertrampf,E. D.,Ruz,M.. Zinc and iron nutrition in Chilean children fed fortified milk provided by the Complementary National Food Program. Nutrition. 2004;20:177-80. | Study design
331 | Torsvik,I. K.,Markestad,T.,Ueland,P. M.,Nilsen,R. M.,Midttun,O.,Bjorke Monsen,A. L.. Evaluating iron status and the risk of anemia in young infants using erythrocyte parameters. Pediatr Res. 2013;73:214-20. | Independent variable
332 | Truswell,A. S.. ABC of nutrition. Infant feeding. Br Med J (Clin Res Ed). 1985;291:333-7. | Study design
333 | Tulchinsky,T. H.,el Ebweini,S.,Ginsberg,G. M.,Abed,Y.,Montano-Cuellar,D.,Schoenbaum,M.,Zansky,S. M.,Jacob,S.,el Tibbi,A. J.,Abu Sha’aban,D.,et al.. Growth and nutrition patterns of infants associated with a nutrition education and supplementation programme in Gaza, 1987-92. Bull World Health Organ. 1994;72:869-75. | Study design, Country
334 | Tympa-Psirropoulou,E.,Vagenas,C.,Dafni,O.,Matala,A.,Skopouli,F.. Environmental risk factors for iron deficiency anemia in children 12-24 months old in the area of Thessalia in Greece. Hippokratia. 2008;12:240-50. | Study design
335 | Ubaidullah,Masood,M. K.,Rafique,M.,Sultan,M. A.. Analysis of risk factors for vitamin D deficiency rickets in children below two years age. Pakistan Paediatric Journal. 2008;32:82-86. | Country
336 | van den Hooven,E. H.,Gharsalli,M.,Heppe,D. H.,Raat,H.,Hofman,A.,Franco,O. H.,Rivadeneira,F.,Jaddoe,V. W.. Associations of breast-feeding patterns and introduction of solid foods with childhood bone mass: The Generation R Study. Br J Nutr. 2016;115:1024-32. | Dependent variable
337 | van den Hooven,E. H.,Heppe,D. H.,Kiefte-de Jong,J. C.,Medina-Gomez,C.,Moll,H. A.,Hofman,A.,Jaddoe,V. W.,Rivadeneira,F.,Franco,O. H.. Infant dietary patterns and bone mass in childhood: the Generation R Study. Osteoporos Int. 2015;26:1595-604. | Dependent variable
338 | van Rheenen,P. F.,de Moor,L. T.,Eschbach,S.,Brabin,B. J.. A cohort study of haemoglobin and zinc protoporphyrin levels in term Zambian infants: effects of iron stores at birth, complementary food and placental malaria. Eur J Clin Nutr. 2008;62:1379-87. | Country
339 | Varea,A.,Malpeli,A.,Etchegoyen,G.,Vojkovic,M.,Disalvo,L.,Apezteguia,M.,Pereyras,S.,Pattin,J.,Ortale,S.,Carmuega,E.,Gonzalez,H. F.. Short-term evaluation of the impact of a food program on the micronutrient nutritional status of Argentinean children under the age of six. Biol Trace Elem Res. 2011;143:1337-48. | Study design, Independent variable
340 | Vazir,S.,Engle,P.,Balakrishna,N.,Griffiths,P. L.,Johnson,S. L.,Creed-Kanashiro,H.,Fernandez Rao,S.,Shroff,M. R.,Bentley,M. E.. Cluster-randomized trial on complementary and responsive feeding education to caregivers found improved dietary intake, growth and development among rural Indian toddlers. Matern Child Nutr. 2013;9:99-117. | Independent variable
341 | Vazquez-Seoane,P.,Windom,R.,Pearson,H. A.. Disappearance of iron-deficiency anemia in a high-risk infant population given supplemental iron. N Engl J Med. 1985;313:1239-40. | Study design
342 | Verma,R.,Khanna,P.,Gaur,D. R.,Meena,Prinja,S.. Assessment of nutritional status and dietary intake of pre-school children in an urban pocket. Internet Journal of Nutrition & Wellness. 2008;6:5p-5p 1p. | Study design, Age
343 | Verma,R.,Meena,Khanna,P.,Varun. Prevalence of anemia and impact of weekly iron-folic acid supplementation on school children in Urban Slums of Haryana, India. Indian Journal of Public Health Research and Development. 2012;3:147-150. | Country, Independent variable
344 | Viljakainen,H. T.,Korhonen,T.,Hytinantti,T.,Laitinen,E. K.,Andersson,S.,Makitie,O.,Lamberg-Allardt,C.. Maternal vitamin D status affects bone growth in early childhood--a prospective cohort study. Osteoporos Int. 2011;22:883-91. | Independent variable
345 | Vir,S. C.,Kalita,A.,Mondal,S.,Malik,R.. Impact of community-based mitanin programme on undernutrition in rural Chhattisgarh State, India. Food Nutr Bull. 2014;35:83-91. | Independent variable, Dependent variable
346 | Vitolo,M. R.,Bortolini,G. A.. Iron bioavailability as a protective factor against anemia among children aged 12 to 16 months. J Pediatr (Rio J). 2007;83:33-8. | Study design, Health Status, Independent variable, Language
347 | Vobecky,J. S.,Vobecky,J.,Shapcott,D.,Demers,P. P.,Blanchard,R.,Fisch,C.. The vitamin status of infants in a free living population. Int J Vitam Nutr Res. 1985;55:205-16. | Independent variable
348 | Vossenaar,M.,Solomons,N. W.. The concept of “critical nutrient density” in complementary feeding: the demands on the “family foods” for the nutrient adequacy of young Guatemalan children with continued breastfeeding. Am J Clin Nutr. 2012;95:859-66. | Dependent variable
349 | Wachs,T. D.,Creed-Kanashiro,H.,Cueto,S.,Jacoby,E.. Maternal education and intelligence predict offspring diet and nutritional status. J Nutr. 2005;135:2179-86. | Independent variable, Dependent variable
350 | Wall,C. R.,Grant,C. C.,Jones,I.. Vitamin D status of exclusively breastfed infants aged 2-3 months. Arch Dis Child. 2013;98:176-9. | Study design, Independent variable
351 | Walravens,P. A.,Chakar,A.,Mokni,R.,Denise,J.,Lemonnier,D.. Zinc supplements in breastfed infants. Lancet. 1992;340:683-5. | Independent variable
352 | Walter,T.,Pino,P.,Pizarro,F.,Lozoff,B.. Prevention of iron-deficiency anemia: comparison of high- and low-iron formulas in term healthy infants after six months of life. J Pediatr. 1998;132:635-40. | Independent variable
353 | Wandel,M.,Fagerli,R. Aa,Olsen,P. T.,Borch-Iohnsen,B.,Ek,J.. Iron status and weaning practices among Norwegian and immigrant infants. Nutrition Research. 1996;16:251-265. | Study design
354 | Wang,Y. Y.,Chen,C. M.,Wang,F. Z.,Jia,M.,Wang,K. A.. Effects of nutrient fortified complementary food supplements on anemia of infants and young children in poor rural of Gansu. Biomed Environ Sci. 2009;22:194-200. | Study design, Independent variable
355 | Wen,X.,Kong,K. L.,Eiden,R. D.,Sharma,N. N.,Xie,C.. Sociodemographic differences and infant dietary patterns. Pediatrics. 2014;134:e1387-98. | Dependent variable
356 | Wharf,S. G.,Fox,T. E.,Fairweather-Tait,S. J.,Cook,J. D.. Factors affecting iron stores in infants 4-18 months of age. Eur J Clin Nutr. 1997;51:504-9. | Study design
357 | Whitehead,R. G.. Principles involved in assessing energy, protein and micronutrient needs during infancy. Proc Nutr Soc. 1986;45:361-7. | Study design
358 | Wijaya-Erhardt,M.,Erhardt,J. G.,Untoro,J.,Karyadi,E.,Wibowo,L.,Gross,R.. Effect of daily or weekly multiple-micronutrient and iron foodlike tablets on body iron stores of Indonesian infants aged 6-12 mo: a double-blind, randomized, placebo-controlled trial. Am J Clin Nutr. 2007;86:1680-6. | Country, Independent variable
359 | Wijga,A.,Vyas,U.,Vyas,A.,Sharma,V.,Pandya,N.,Nabarro,D.. Feeding, illness and nutritional status of young children in rural Gujarat. Hum Nutr Clin Nutr. 1983;37:255-69. | Study design, Dependent variable
360 | Winick,M.. Pediatric nutrition: introduction. Pediatr Ann. 1981;10:17-8. | Study design
361 | Winkelstein,M. L.. Overfeeding in infancy: the early introduction of solid foods. Pediatr Nurs. 1984;10:205-8, 236. | Study design, Dependent variable
362 | Yip,R.,Reeves,J. D.,Lonnerdal,B.,Keen,C. L.,Dallman,P. R.. Does iron supplementation compromise zinc nutrition in healthy infants?. Am J Clin Nutr. 1985;42:683-7. | Study design, Independent variable
363 | Zhang,J.,Shi,L.,Chen,D. F.,Wang,J.,Wang,Y.. Effectiveness of an educational intervention to improve child feeding practices and growth in rural China: updated results at 18 months of age. Matern Child Nutr. 2013;9:118-29. | Dependent variable
364 | Ziegler,E. E.,Fomon,S. J.,Nelson,S. E.,Rebouche,C. J.,Edwards,B. B.,Rogers,R. R.,Lehman,L. J.. Cow milk feeding in infancy: further observations on blood loss from the gastrointestinal tract. J Pediatr. 1990;116:11-8. | Independent variable
365 | Ziegler,E. E.,Nelson,S. E.,Jeter,J. M.. Iron stores of breastfed infants during the first year of life. Nutrients. 2014;6:2023-34. | Independent variable
366 | Ziegler,E. E.,Nelson,S. E.,Jeter,J. M.. Iron supplementation of breastfed infants from an early age. Am J Clin Nutr. 2009;89:525-32. | Independent variable
367 | Ziegler,E. E.,Nelson,S. E.,Jeter,J. M.. Iron supplementation of breastfed infants. Nutr Rev. 2011;69 Suppl 1:S71-7. | Study design
368 | Ziegler,E. E.. Milks and formulas for older infants. J Pediatr. 1990;117:S76-9. | Study design, Dependent variable