# List of abbreviations

Abbreviation: Full name
BF: Breast fed
BMIZ: Body mass index z-score
CF: Complementary feeding
CFB: Complementary food and beverage
DXA: Dual-energy X-ray absorptiometry
EBF: Exclusively breast-fed
EFF: Exclusively formula fed
FEG: Federal expert group
FF: Formula fed
FFM: Fat-free mass
FM: Fat mass
FMZ: Fat mass z-score
HAZ: Height-for-age z-score
HC: Head circumference
HHS: Department of Health and Human Services
LAZ: Length-for-age z-score
NEL: Nutrition Evidence Library
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
P/B-24: Pregnancy and Birth to 24 Months Project
RCT: Randomized controlled trial
TEC: Technical Expert Collaborative
USDA: United States Department of Agriculture
WAZ: Weight-for-age z score
WC: Waist circumference
WHZ: Weight-for-height z score
WLZ: Weight-for-length z score