# APPENDIX

The table below describes study and sample characteristics from the included articles, organized by study design then alphabetical order of the first author’s last name.

Supplemental Table S4 Description of the evidence examining timing of introduction of CFB and growth, size, and body composition

Randomized controlled trials
Bainbridge, 1996; Randomized Controlled Trial; U.S.; [underlined: Sample Size]:; Baseline N: 41; Analytic N: 41; Attrition: 0%; Power Analysis/Sample Size Calculation: NR; [underlined: Sex:]; ~49% Female; [underlined: Race/Ethnicity]:; 73.2% White, 26.8% Black; [underlined: Background Diet]:; All FF with same formula from birth to 16wk | [underlined: Intervention/Exposure:]; Age of CFB introduction: CFB at 16wk vs. EFF until 26wk; CFB: Rice cereal from 16-26wk; Both groups were FF and the EFF group continued exclusive use of formula from 16-26wk; Age: 4mo; Assessment Methods:; Food record, 3d; [underlined: Outcomes:]; Weight; Length; Body composition (Adiposity); Age: 16wk, 26wk, 16-26wk; Assessment Methods:; Body composition: Skinfold thickness: calipers; abdominal, MUAC, triceps, mid-thigh, chest, subscapular, suprailiac; Weight, length: NR, digital scale and length board; HC: NR; [underlined: Confounders accounted for:]; N/A; Other: At baseline, reported NSD in sex, race/ethnicity, birth weight, gestational age; and all were FF | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on education, SES, or maternal age, early CFB group was 1cm shorter than EBF group at baseline; Participants (infants/mothers) were not blinded; Cannot determine if investigators were blinded; For technical reasons due to sample size limitations, outcome measurements were available for n:23 in group receiving CFB at 16wk group and n:18 in the group delaying CFB to 26wk; Sample size was very small
Jonsdottir, 2012; Randomized Controlled Trial; Iceland; [underlined: Sample Size]:; Baseline N: 119; Analytic N: 100; Attrition: 16%; Sample Size Calculation: N=50 (to detect differences in Fe status); [underlined: Sex:]; 55% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; All infants were EBF up to 4mo, and continue to be BF through 6mo | [underlined: Intervention/Exposure:]; EBF infants were randomized to one of 2 groups:; EBF: Remained exclusively BF until 6mo; CFB: Receive CFB starting at age 4mo; CFB: Foods other than BM; Diaries indicated every new food added to CFB infant diet from 4mo to 6mo; Age: 4mo; Assessment Methods:; Maternal diet diary; Food record, 3d, weighed; [underlined: Outcomes:]; Weigh; Length; HC; Age: birth-6mo; 4-6mo; Assessment Methods:; Weight: Seca scale; used for WAZ by WHO standards; Length: measuring board; used for LAZ by WHO standards; HC: non-stretchable tape; [underlined: Confounders accounted for:]; Feeding practices: All EBF; Gestational age: All full-term; Other: Delivery mode | [underlined: Limitations:]; Cannot determine if investigators or outcome assessors were blinded; Participants were not blinded; Outcome assessment methods were not validi/reliable (non-duplicate and various assessors; data collected in routine health care visits at health centers)
Jonsdottir, 2013; Randomized Controlled Trial; Iceland; [underlined: Sample Size]:; Baseline N = 119 (N=100 completed the intervention); Analytic N = 54-78; Attrition = 34.5%; Power Analysis and Sufficient Sample Size: N=66 (to detect an 11.2 point difference in the Brigance screening test at 30-35mo, 80% power); [underlined: Sex:]; 54.5% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; In Iceland, 50% of infants are EBF through 4mo and 35% through 5mo | [underlined: Intervention/Exposure:]; EBF infants were randomized to one of 2 groups:; EBF: Remained exclusively BF until 6mo; CFB: Receive CFB starting at age 4mo; CFB: Foods other than BM; Diaries indicated every new food added to CFB infant diet from 4mo to 6mo; Age: 4mo; Assessment Methods:; Maternal diet diary; Food record, 3d, weighed; [underlined: Outcomes:]; HC; Age: birth-18mo; Assessment Methods:; HC: gain; measured with non-stretchable tape (Jonsdottir, 2012); [underlined: Confounders accounted for:]; Feeding practices: All EBF; Gestational age: All full-term; Other: Delivery mode | [underlined: Limitations:]; Cannot determine if investigators or outcome assessors were blinded; Participants were not blinded; Cannot determine validity/reliability of outcome measurements (non-duplicate and various assessors; lack of detail for HC; data collected in routine health care visits at health centers); Authors note that the analysis my have been underpowered (small sample size) to detect potential small differences in developmental outcomes
Jonsdottir, 2014; Randomized Controlled Trial; Iceland; [underlined: Sample Size]:; Baseline N: 119; Analytic N: 100; Attrition: 16%; Sample Size Calculation: N=50 (to detect differences in Fe status); [underlined: Sex:]; 54.5% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; In Iceland, 50% of infants are EBF through 4mo and 35% through 5mo | [underlined: Intervention/Exposure:]; EBF infants were randomized to one of 2 groups:; EBF: Remained exclusively BF until 6mo; CFB: Receive CFB starting at age 4mo; CFB: Foods other than BM; Diaries indicated every new food added to CFB infant diet from 4mo to 6mo; Age: 4mo; Assessment Methods:; Maternal diet diary; Food record, 3d, weighed; [underlined: Outcomes:]; Weight status; Weight; Length; HC; Age: 18, 29-38mo; Assessment Methods:; Weight status: risk for overweight classified as >1SD above BMI-for-age (WHO); Overweight classified as >2SD above; Obesity classified as >3SD; Weight: via Seca scale; WAZ and Δ WAZ by WHO standards; Length: via measuring board/body meter; LAZ and Δ LAZ by WHO standards; HC: non-stretchable tape; [underlined: Confounders accounted for:]; Feeding practices: All EBF; Gestational age: All full-term; Other: Delivery mode | [underlined: Limitations:]; Groups differed in mode of delivery, which was not adjusted for in analyses; Cannot determine if investigators or outcome assessors were blinded; Participants were not blinded; Cannot determine validity/reliability of outcome measurements (non-duplicate and various assessors; data collected in routine health care visits at health centers); Relatively small sample-size
Wells, 2012; Randomized Controlled Trial; Iceland; [underlined: Sample Size]:; CFB Group Baseline N: 61; EBF Group Baseline N: 58; CFB Group Analytic N: 50; EBF Group Analytic N: 50; Attrition: 16%; Power Analysis and Sufficient Sample Size: N=50/group to detect differences of 75 g/d with 80% power and 5% significance; [underlined: Sex:]; 50% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; EBF: 100% at baseline | [underlined: Intervention/Exposure:]; CFB Group: Advised to introduce CFB at 4mo (no specific advice regarding type/amount of CFB to introduce); EBF Group: Advised to exclusively BF through 6mo; Age: 4-6mo; Assessment Methods:; Food records, 3d; [underlined: Outcomes:]; Body composition (Adiposity; BMI); Weight; Length, HCz; Age: 6mo; Assessment Methods:; Body composition:; - Lean/fat mass: Calculated based on total body water; - BMI: Calculated using measured weight, length; Weight: Measured by study personnel; Length: Measured by study personnel, recumbent; HC: z-score, measured by study personnel; [underlined: Confounders accounted for:]; None | [underlined: Limitations:]; Groups differed at baseline on multiparity, vaginal delivery; cannot determine whether these differences were adjusted for in subsequent analyses; Participants, outcome assessors were not blinded; cannot determine whether investigators were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., single vs multiple measures); Adequacy of statistical methods insufficient (no description of which potential confounders were included in analyses); Data from the RCT in Jonsdottir, 2012; Jonsdottir, 2013; Jonsdottir, 2014
Prospective cohort studies
Abraham, 2012; Prospective Cohort Study; Scotland; [underlined: Sample Size]:; Baseline N: 5,217; Analytic N: 4,493 (completed survey at 9-12mo); 3,994 (completed outcomes at 45-48mo); Attrition: 13.9%; Power Analysis: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; 4% non-white ethnic group (Bradshaw, 2007); [underlined: Background Diet]:; 61.0% ever BF, 39.0% never BF | [underlined: Intervention/Exposure:]; Age of CFB introduction: 0-3 vs. 4-5; 0-3 vs. 6-10mo; Age: 0-24mo; Assessment Methods:; Caregiver self-report at 9-12mo; [underlined: Outcomes:]; Weight status (Overweight/obesity); Age: 45-48mo; Assessment Methods:; Weight status: risk of overweight/obese BMI >/= 1.04, or not overweight/obese</= 1.04 (UK 1990 ref. curves BMIZ cut-off) Weight, height: NR; [underlined: Confounders accounted for:]; SES: X; Birth size: X (Birth weight) | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Key confounders from the analytic framework were NR or adjusted for in analyses including sex, race/ethnicity, maternal age, or gestational age; Cannot determine if outcome assessors were blinded, primary interviewers were unblinded; Other: IV/Exposure was self-report; Bradshaw, 2007 summarizes Sweep 1 baseline characteristics
Agras, 1990; Prospective Cohort Study; U.S.; [underlined: Sample Size]:; Baseline N: 99; Analytic N: 54; Attrition: 45%; Power Analysis/Sample Size Calculation: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF and/or FF | [underlined: Intervention/Exposure:]; Age of CFB introduction: Weeks, continuous; Age: 2, 4, 12, 20wk; Assessment Methods:; Maternal report; [underlined: Outcomes:]; BMI; skinfold thickness; Age: 1, 2, 3 a/o 6y; Assessment Methods:; Body composition: skin-fold thickness, and log BMI (more normally distributed) calculated from measures; Weight, height: measured in the laboratory; [underlined: Confounders accounted for:]; Education: X; Sex: X; Feeding practices: X; Birth size: X (Birth BMI); Other: parent BMI, # feedings/d; sucking pressure, interval of sucking bursts, caloric intake during suckling, active feeding time | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Due to limited information provided about methods,; Did not adjust for potential key confounders (SES, maternal age, race/ethnicity, gestational age); Did not account for high attrition rate (~45%); Log birth BMI was used as birth size variable in regression; Only assessed infant feeding practices through 5mo of age; Cannot rule out reverse causality (vigorous BF may influence timing CFB introduction)
Atkins, 2016; Prospective Cohort Study; Australia; [underlined: Sample Size]:; Baseline N: 542; Analytic N: 423; Attrition: 22%; Power Analysis/Sample Size Calculation: NR; [underlined: Sex:]; ~47% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 2% never BF, 46% BF at 9mo, 9% BF at 20mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <6 vs. >6mo; Age: 3mo; Assessment Methods:; 3, 24-h recalls by parent; [underlined: Outcomes:]; Weight; Height; Age: 9mo, 20mo; Assessment Methods:; Weight, length: Measured by trained staff using digital scales and calibrated measuring mat; [underlined: Confounders accounted for:]; None | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine relability/validity of outcome assessment (used measuring mat, not length board); Did not adjust for any potential key confounders (education, SES, sex, maternal age, race/ethnicity, feeding practices, birth size, gestational age); Cannot determine if analyses adjusted for differences in birth weight and length differed between groups; weight/length at 9mo not shown) *Weight/length were secondary oucomes
Ay, 2008; Prospective Cohort Study; The Netherlands; [underlined: Sample Size]:; Baseline N: 1232; Analytic N: 1012; Attrition: 17.9%; Power Analysis/Sample Size Calculation: NR; [underlined: Sex:]; 48.2% Female; [underlined: Race/Ethnicity]:; 100% “Dutch ethnicity”; [underlined: Background Diet]:; ~90% ever BF, duration of BF = ~5mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <5 or >5mo; CFB: Fruit snack; Age: 2, 6, and 12mo; Assessment Methods:; Caregiver questionnaire; [underlined: Outcomes:]; Body composition (Adiposity); Age: 24mo; Assessment Methods:; Body composition: sum of skinfold thickness (biceps, triceps, suprailiacal, subscapular) measured by study personnel using calipers; [underlined: Confounders accounted for:]; Education: X; Sex: X; Maternal age: X; Gestational age: X; Other: Smoking | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Did not adjust for any key confounders (SES, race/ethnicity/feeding practices, birth size)
Baird, 2008; Prospective Cohort Study; U.K.; [underlined: Sample Size]:; Baseline N = 1,973; Analytic N = 1,740 at 6mo; 1335 at 12mo; Attrition = 11.8%; 32.4% at 12mo; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 46.9% female; [underlined: Race/Ethnicity]:; 94% white; [underlined: Background Diet]:; 0-6mo: 7.5% BF; ~21% FF, ~71.5% MF combination of BF and FF assessed via caregiver-report at 6mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: early (<3, 3, at 4mo) or later (5mo+); CFB: Any other food aside from HM or HM substitute; 99% introduced CFB <5mo; Age: 12mo; Assessment Methods:; Timing: Maternal report; Type: FFQ over 7d at 6mo; FFQ over 28d at 12mo; Dietary patterns identified by PCA; [underlined: Outcomes:]; Body composition; Weight; Length; Age: 6mo, 0-6mo; Assessment Methods:; Weight: digital scale; crude and change in weight SD score from 0-6mo and 6-12mo; Length: infantometer; crude and change in length SD score from 0-6mo and 6-12mo; Body composition: triceps and subscapular skinfold calipers; crude and thickness SD score from 0-6mo and 6-12mo; [underlined: Confounders accounted for:]; Education: X; Sex: X; Gestational age: X; Other: Parity; Smoking | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline; Unclear whether outcome assessors were blinded to the infants’ feeding histories; Did not adjust for potential key confounders (SES, maternal age, race/ethnicity, feeding practices, birth size, gestational age); BF duration and infant diet was retrospectively self-reported by mothers at 6 and 12mo, thus may have been biased; ethnic minorities were underrepresented in this sample.
Baker, 2004; Prospective Cohort Study; Denmark; [underlined: Sample Size]:; Baseline N = 5,845; Analytic N = 3,768; Attrition = 36.5%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; ~49.5% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; Duration of full BF: ~16wk; Duration of BF: 32wk | [underlined: Intervention/Exposure:]; Age of CFB introduction: <16 vs. >16wk; CFB: Mush or porridge; Age: 12mo; Assessment Methods:; Maternal report; [underlined: Outcomes:]; Weight; Age: Birth-1y; Assessment Methods:; Weight: gain birth-1y based on maternal report from the “green book” health record from physicians; [underlined: Confounders accounted for:]; Education: X; SES: X (income); Sex: X; Maternal age: X; Feeding practices: X; Birth size: X (Birth weight); Gestational age: X; Other: Parity; Delivery mode; Infant age; Maternal occupation; Spouse; Gestational weight gain; Smoking; Infant length at 1y (reverse causality) | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on race/ethnicity; Outcome assessors were not blinded-both the independent and dependent variables were measured using non-validated methods (maternal self-report); Did not account for high loss to follow-up (>35%); Did not adjust for potenital key confounder of race/ethnicity; Did not collect types-amounts of CFB or composition, or energy expenditure, or timing of introduction of formula
Barrera, 2016; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N: 1542; Analytic N: 1181; Attrition: ~23.4%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 50.1% Female; [underlined: Race/Ethnicity]:; 88.3% non-Hispanic white; 3% non-Hispanic black; 5% Hispanic; 2.3% other; [underlined: Background Diet]:; NR | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4, 4–<6, and ≥6mo; CFB: Solid foods included dairy foods other than milk (e.g., yogurt, cheese, and ice cream); soy foods other than soy milk (e.g. Tofu, frozen soy desserts); baby cereal; other cereals and starches (e.g., breakfa; Age: 4-6mo; Assessment Methods:; Caregiver report; [underlined: Outcomes:]; Weight status; Age: 6y; Assessment Methods:; Weight status: risk of obesity based on age- and sex-specific BMI%tile 2000 CDC; BMI calculated from height and weight measured by mothers; [underlined: Confounders accounted for:]; Education:X; SES: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X; Gestational age: X; Other: Parity; Maternal BMI; Marital status; Infant intake of CFB | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Outcome assessors were not blinded, both the independent and dependent variables were maternal self-report; Non-validated measures used to assess outcome; Maternal self-report of IV/Exposure and Outcomes; Sample not nationally representative
Barton, 2002; Prospective Cohort Study; U.S.; [underlined: Sample Size]:; Baseline N = 52; Analytic N = 52; Attrition = 0%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 46% BF, 54% FF at birth; 33% BF, 67% FF at 1-2mo; 83% received CFB <4mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4, >4mo; CFB: “Solid foods” including infant cereal, vegetables, fruits, and <6oz fruit juice/d; Age: 4-6mo; Assessment Methods:; Caregiver report; [underlined: Outcomes:]; Weight; Length; HC; Age: 1-2mo; 4-6mo; Assessment Methods:; Weight: measured by study personnel on balance-beam scale; Height: measured by trained personnel, on standard length board; HC: measured by study personnel with nonfabric measuring tape; [underlined: Confounders accounted for:]; None; Other: Weights, lengths, and HC at baseline NSD between groups | [underlined: Limitations:]; Cannot determine whether groups differed at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Length of follow-up varied from 4 to 6mo of age; Cannot determined validity/reliability of measures used to assess outcomes (single vs. multiple measures); Did not adjust for any potential key confounders (including education, SES, sex, maternal age, race/ethnicity, feeding practices, birth size, gestational age); Post-hoc tests suggest marginal significance; Did not adjust for baseline values though weight, length, and HC at 1-2mo were similar between groups; Groups were unbalanced (40 infants in the CFB <4mo group vs. 8 infants in the >4mo group); Cannot rule out reverse causality (group already not gaining weight well) Very short term followup
Butte, 2000; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N = 76; Analytic N = 72; Attrition = 5.3%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 56.6% Female; [underlined: Race/Ethnicity]:; 72.4% White, 9.2% Black, 14.5% Hispanic, 3.9% Asian; [underlined: Background Diet]:; BF and FF infants were analyzed separately; Mean age of introduction of solids was ~5mo for BF infants and ~4mo for FF infants | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous; CFB: Solids other than formula, milk, juice, water, and vitamin-mineral supplements; Age: 3, 6, 12, and 24mo; Assessment Methods:; Food record, 3d, weighed; [underlined: Outcomes:]; Body composition; Weight; Length; Circumferences (head, chest, arm, thigh); Age: 6-24mo; Assessment Methods:; Body composition:; - Fat mass, fat-free mass calculated using a multicomponent body composition model based on total body water by deuterium dilution, total body potassium by whole body counting, and bone mineral content by DXA; - Skinfold thickness (triceps, subscapular, flank, quadriceps): measured by study personnel; Weight, length, circumferences (head, chest, arm, thigh) measured by study personnel; [underlined: Confounders accounted for:]; Sex: X; Feeding practices: X; Other: Baseline anthropometric values | [underlined: Limitations:]; Cannot determine whether groups differed at baseline on key characteristics; Did not adjust for potential key confounders (education, SES, maternal age, race/ethnicity, birth size, gestational age)
Cantoral, 2016; Prospective Cohort Study; Mexico; [underlined: Sample Size]:; Baseline N: 622 (enrolled in F/U); Analytic N: 227; Attrition: ~64%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 54% female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 31% at least partial BF; 73% introduced to SSB <12mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: ≤12 vs >12mo; CFB: SSB: sum of daily intake of soda, commercial fruit drinks, flavored water with sugar; Not including natural fruit or vegetable juice; Age: 12mo; every 6mo until 5y; at 8-14y; Assessment Methods:; 116-item FFQ; [underlined: Outcomes:]; Weight status; WC; Age: 8-14y; Assessment Methods:; Weight status: risk of obesity classified as BMI>2 SD of z-score; BMI from measured weight (digital scale to 0.1kg) and height (stadiometer to 0.1cm); WC: measuring tape to 0.1cm for abdominal obesity: WC≥ 90th %tile; [underlined: Confounders accounted for:]; SES: X; Sex: X; Feeding practices: X; Other: non-SSB intake, TV watching, physical activity, maternal obesity at 12mo post-partum | [underlined: Limitations:]; Cannot determine whether groups differed at baseline on key characteristics; Cannot determine if outcome assessors were blinded; Did not account for high attrition rate; Did not adjust for key confounders of education, maternal age, race/ethnicity, birth size or gestational age; Risk for measurement error associated with FFQ; Assumes that SSB intake was constant during the months evaluated on FFQ
Carruth, 2000; Prospective Cohort Study; U.S.; [underlined: Sample Size]:; Baseline N = 98; Analytic N = 94; Attrition = 4.1%; Power Analysis and Sufficient Sample Size: Use of an incomplete block design maintained statistical power; [underlined: Sex:]; 48.0% female (Skinner, 1997); [underlined: Race/Ethnicity]:; 100% White; [underlined: Background Diet]:; 83% any BF, 33% EBF at 4mo, 33% MF at 4mo; 12% EBF at 6mo; ~64% CFB by 4mo; Median age for introducing CFB: cereal 4.0 (range .50–6.5 mo), juice 4.50 (1–11 mo), fruit 5.0 (.50–8.2 mo), vegetables 5.5 (1–7.7 mo) and the food cluster (mixed foods, table foods, meat) 7.0 (3–12 mo) | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous; CFB: supplementary foods included vegetables, cereal, juice, fruit, and food cluster (meat, mixed food, or table food); Age: 2, 3, 4, 6, 8, 10, 12, 16, 20, and 24mo; Assessment Methods:; 24h recall; [underlined: Outcomes:]; Weight; Length; Age: 2-8mo; 12-24mo; Assessment Methods:; Weight: slope (kg/mo); standard protocol; Length: slope (cm/mo); standard protocol; Interview schedules were done using an incomplete block design, such that the number of times measures were taken for each infant 3-5 times from 2 to 10mo, and 2-4 times from 12 to 24mo; [underlined: Confounders accounted for:]; Sex: X; Other: Final model 2-8mo weight slope: gender; Final model 2-8mo length slope: gender; Final model 2-8mo rate of change weight: gender, length slope; Final model 12-24mo weight gain: length, pre-existing weight | [underlined: Limitations:]; Cannot determine whether groups differed at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine adequacy of statistical methods (previous versions of regression models not described, data not shown); Did not adjust for potential key confounders (education, SES, maternal age, race/ethnicity, birth size, or gestational age); Limited generalizability (small sample of white middle- to upper class subjects from TN); Results section reports that only age of introduction to vegetables and food cluster remained as significant predictors in rate of change in relative weight but that ages of CFB were not significant predictors in weight gain 12-24mo; Unclear if cereal ≤4 or >4mo was analyzed in relation to weight outcomes (reports in relation to illness). Final models reported significant predictors of weight change but post-hoc removal of length resulted in models becoming no longer significant; Cannot rule out reverse causality
de Beer, 2015; Prospective Cohort Study; The Netherlands; [underlined: Sample Size]:; Baseline N: 7863 (gave birth; N: 5551 with data; N:3321 attended 5-6y visit); Analytic N: 2227; Attrition: ~72%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; ~49% Female; [underlined: Race/Ethnicity]:; ~78% Dutch; ~2.4% Surinamese; ~2% Turkish; ~4% Moroccan; ~13% Other; [underlined: Background Diet]:; ~23% <1mo BF; ~27% BF 1-3mo; ~31% BF 3-mo; ~19% BF >6mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4, 4-6, >6mo; Age: 1-11mo; Assessment Methods:; Monitored at check-ups; [underlined: Outcomes:]; Weight; Height; Body composition; z-score, height z-score, fat-mass z-score; BMIZ; Age: 6-12mo; 5-6y; Assessment Methods:; Body composition:; - BMIZ calculated based on measured weight and height; z-score; - Fat mass (FMZ), fat free mass (FFMZ) z-scores: calculated based on total body water from measured arm-leg bioelectrical impedance; Weight, height: measured via scale, length board, and portable stadiometer; ‘Conditional’ sizes were created by standardized residuals derived from regressions of current and prior height and weight measures. Conditional height and weight represent a child’s deviation from expected size and growth; [underlined: Confounders accounted for:]; Education: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X (Birth weight); Gestational age: X; Other: Current age; Childhood conditional height (12 months—5–6 years); Conditional height and weight during all periods in infancy; Maternal pre-pregnancy BMI; Maternal Height; Smoking; Alcohol; Hypertension; Pregnancy duration as gestational age | [underlined: Limitations:]; Cannot determine whether groups differed at baseline on key characteristics; Cannot determine if outcome assessors or investigators were blinded; Did not adjust for potential key confounder (SES); High-attrition rate not accounted for; High loss to follow-up and group analyzed differed from original cohort in ways NR; Anthropometric measurements less precise than DEXA; Reverse causality of infant feeding and growth; Results reported in abstract and discussion differ from results reported in tables; No cut-off/P-values were reported in tables related to analyses
Durmus, 2012; Prospective Cohort Study; The Netherlands; [underlined: Sample Size]:; Baseline N: 1106; Analytic N: 779; Attrition: 29.6%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 49% female; [underlined: Race/Ethnicity]:; 100% “Dutch ethnicity”; [underlined: Background Diet]:; 87.5% ever BF; ~4.5mo BF duration | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4, 4-5, >5mo; CFB: Age that a fruit or vegetable snack was given; Age: 2, 6, and 12mo; Assessment Methods:; Caregiver questionnaire; [underlined: Outcomes:]; Body composition (Adiposity); Age: 6mo, 24mo; Assessment Methods:; Body composition:; - Subcutaneous fat mass via skinfold thickness (biceps, triceps, suprailiacal, subscapular) measured by study personnel using calipers; [underlined: Confounders accounted for:]; Education: X; Sex: X; Feeding practices: X; Birth size: X (Birth weight); Gestational age: X; Other: Maternal BMI, Smoking; Parity; Current height; Observer | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on all key characteristics; Cannot determine whether outcome assessors were blinded; Did not assess the impact of high loss to follow-up (~27%); Did not adjust for key confounders (SES, maternal age, race/ethnicity); BF information only available in 78% of sample; CFB included only a fruit or vegetable snack and other products could have been introduced; Homogenous, highly-educated sample; Limited generalizability
Durmus, 2014; Prospective Cohort Study; The Netherlands; [underlined: Sample Size]:; Baseline N: 6054; Analytic N: 5063; Attrition: 16.4%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 50.2% Female; [underlined: Race/Ethnicity]:; 100% “Dutch ethnicity”; [underlined: Background Diet]:; 92.4% ever BF; 20.4% EBF to 4mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4, 4-4.9, ≥5mo; CFB: Age that a fruit or vegetable snack was given; Age: 2, 6, and 12mo; Assessment Methods:; Caregiver questionnaire; [underlined: Outcomes:]; Weight status; Body composition; WC (abdominal fat); Age: 6y; Assessment Methods:; Weight status: risk of overweight or obesity based on IOTF categories for BMI; Body composition:; - Adiposity: total fat mass, android-gynoid ratio (DXA); - BMI: calculated from measured height/weight (stadiometer/mechanical scale); Abdominal/WC: abdomial fat via ultra-sound; [underlined: Confounders accounted for:]; Education: X; Sex: X; Maternal age: X; Race/ethnicity: X; Birth size: X; Gestational age: X; Other: Child age, Child height; Parity; Maternal BMI, Smoking; TV watching | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on all key characteristics; Cannot determine whether outcome assessors were blinded; Did not adjust for key confounders (SES or feeding practices); Did not collect information on BM consumption or composition
Ejlerskov, 2015; Prospective Cohort Study; Denmark; [underlined: Sample Size]:; Baseline N = 330; Analytic N = 233; Attrition = 29.4%; Power Analysis and Sufficient Sample Size: N=260 to detect differences in growth; [underlined: Sex:]; 52.4% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; EBF: 126d, median (IQR=91-152); fully BF at 4mo: 67.8%; PBF at 9mo: 42.5%; median g/day formula at 9mo: 169 (IQR=0-410); median mo introduction of solids: 4.0 (IQR=4.0-5.0) | [underlined: Intervention/Exposure:]; Age of CFB introduction: earliest age receiving one of 19 food categories in mo;; Age: 9, 18, and 36mo; Assessment Methods:; Parental interview; [underlined: Outcomes:]; Body composition; Age: 36mo (±3); Assessment Methods:; Body composition:; - Fat free mass index, fat mass index: calculated from BIA and DXA measures for fat mass and fat free mass; [underlined: Confounders accounted for:]; Education: X; Sex: X; Feeding practices: X (Table 7); Birth size: X; Other: WAZ 0-5mo; Maternal BMI | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine validity and reliability of dietary assessment; Did not assess the impact of high loss to follow-up (~29%); Did not adjust for key confounders such as SES, maternal age, race/ethnicity, or gestational age; Insufficient power; prediction error of FFM and FM from BIA vs. DXA; age of introduction to CFB collected retrospectively; Fully BF for 6mo group drove results;
Fairley, 2015; Prospective Cohort Study; United Kingdom; [underlined: Sample Size]:; Baseline N: 1707; Analytic N: 987; Attrition: ~42%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; 39% White British; 48% Pakistani; 13% Other; [underlined: Background Diet]:; 27% never BF; 26.3% BF <1mo; 18.5% BF 1-4mo; 28.2% BF >4mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <17 or ≥ 17wk; Age: 6 and 12mo; Assessment Methods:; Caregiver questionnaire; [underlined: Outcomes:]; Weight status; body composition; Age: 36mo; Assessment Methods:; Weight status: relative risk of overweight classified as BMIZ ≥ 85th %tile; Body composition: BMI z-scores by WHO, 2006 standards from weight and height; [underlined: Confounders accounted for:]; Education: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X; Gestational age: X; Other: Parity; Delivery Mode | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment; Did not assess the impact of high loss to follow-up (~42%); Did not adjust analyses for SES; Insufficient power to examine Obesity; Multiple testing not accounted for
Fawzi, 1997; Prospective Cohort Study; Israel; [underlined: Sample Size]:; Baseline N: 1041; Analytic N: 351; Attrition: 66%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; 49% Israel 51% immigrants from North African country; [underlined: Background Diet]:; 92.3% EBF at birth; 35.9% EBF at 1mo; 19.6% EBF at 2mo; 7.3% EBF at 3mo; 0.7% EBF at 6mo | [underlined: Intervention/Exposure:]; Age of CFB introduction at 1, 2, or 3mo vs. EBF; CFB: solids exclusively; Age: Birth, 1-3mo; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Weight; Age: 2mo, 3mo; Assessment Methods:; Weight: gain; beam-balance scales to 0.1kg; [underlined: Confounders accounted for:]; Education: X; Sex: X; Feeding practices: X (in analyses); Birth size: X (Birth weight, weight at first prenatal visit); Other: Maternal height | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment; Did not adjust for potential confounders of SES, maternal age, race/ethnicity, or gestational age; Did not account for only 2 infants being EBF at 6mo so could not do comparisons as planned; Cannot rule out reverse causality; Limited generalizability due to immigrant sample; Short-term follow-up
Ferris, 1980; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N: 92; Analytic N: 92; Attrition: 0%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 100% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 43.5% BF alone; 13% BF+solids; 11% FF alone; 21.7% FF+solids | [underlined: Intervention/Exposure:]; Age of CFB introduction: at 2mo or >2mo; CFB: CFB+FF vs. FF alone; Age: 2mo; Assessment Methods:; Food record, 3d and diary; [underlined: Outcomes:]; Body composition; Weight; Length; Age: birth-6mo; Assessment Methods:; Body composition: weight/length^2^ from measures; Weight, and height with scale and infantometer; [underlined: Confounders accounted for:]; SES: X; Sex: X (all female); Birth size: X; Other: Income, maternal smoking, parent weight, and parity at baseline similar between groups | [underlined: Limitations:]; Cannot determine whether outcome assessors were blinded; Did not adjust analyses for potential key confounders (education, race/ethnicity, or gestational age); Sample was 100% female - male participants were to be reported elsewhere; Feeding practices part of analyses
Flores, 2013a; Prospective Cohort Study; U.S.; [underlined: Sample Size]:; Baseline N: 14000; Analytic N: 6800; Attrition: ~51%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 48.9% Female; [underlined: Race/Ethnicity]:; 54% White; 25% Latino; 14% African- American; 2.7% Asian/PI; 0.4% AI/AN; 3.8% Multi; [underlined: Background Diet]:; Average duration BF ~3.7mo Average introduction to formula ~3.5mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous, mo; <3.5 vs. ≥3.5mo; CFB: solid food a/o finger food; Age: NR; Assessment Methods:; Caregiver a/o teacher report; [underlined: Outcomes:]; Weight status; Age: Kindergarten entry (~7.5y); Assessment Methods:; Weight status: prevalance of overweight, based on age- and sex-specific BMI≥ 85th %tile; BMI by CDC standards, calculated from measured weight, and height (in triplicate with a digital scale and stadiometer); [underlined: Confounders accounted for:]; None; Recursive partioning analyses accounted for: BMI at preschool age and at 2y, race/ethnicity, maternal gestational diabetes, birth weight | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Did not assess the impact of high loss to follow-up (~51%); Did not adjust analyses for potential key confounders (education, SES, sex, maternal age, or gestational age) RPA selects highest significance for binary split based on reducing variance not by P values; groups varied by outcome status in all risk factors assessed in bivariate analyses
Flores, 2013b; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N: 14000; Analytic N: 6800; Attrition: ~51%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 48.9% Female; [underlined: Race/Ethnicity]:; 54% White; 25% Latino; 14% African- American; 2.7% Asian/PI; 0.4% AI/AN; 3.8% Multi; [underlined: Background Diet]:; Average duration BF ~3.7mo Average introduction to formula ~3.5mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous, mo; CFB: solid food a/o finger food; Age: NR; Assessment Methods:; Caregiver a/o teacher report; [underlined: Outcomes:]; Weight status; Age: Kindergarten entry (~7.5y); Assessment Methods:; Weight status: prevalance of obesity classified as BMI≥99th %tile; age- and sex- specific BMI by CDC standards calculated from weight, and height, which were measured in triplicate with a digital scale and stadiometer; [underlined: Confounders accounted for:]; Feeding practices: X (in model) | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Did not assess the impact of high loss to follow-up (~51%); Did not adjust analyses for potential confounders (education, SES, sex, maternal age, race/ethnicity, birth size or gestational age); Lack of information provided on intervention/exposure measurement; Feeding practices included in model
Forsyth, 1993; Prospective Cohort Study ; Scotland; [underlined: Sample Size]:; Baseline N: 671; Analytic N: 584 at 8wk; 576 at 13wk; 544 at 26wk; 548 at 52wk; 392 at 104wk; Attrition: ~13% at 8wk; ~14% at 13wk; ~19% at 26wk; ~18% at 52wk; ~42% at 104wk; Sample Size Calculation: NR; [underlined: Sex:]; ~52% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 14% EBF, 19.3% PBF, 66% MF | [underlined: Intervention/Exposure:]; Age of CFB introduction: <8, 8-12, or >12wk; Age: 8-12wk (~2-3mo); Assessment Methods:; Maternal questionnaire; [underlined: Outcomes:]; Weight; Age: 4, 8, 13, 26, 52, 104wk; Assessment Methods:; Weight: weighing machine with 20g divisions; [underlined: Confounders accounted for:]; SES: X; Sex: X; Maternal age: X; Feeding practices: X; Birth size: X (Birth weight); Gestational age: All full-term; Other: Smoking; Atopy risk | [underlined: Limitations:]; Groups differed at baseline on key characteristics but analyses were not adjusted for differences; Cannot determine reliability/validity of outcome assessment; Did not adjust analyses for potential key confounders (education, race/ethnicity, or gestational age).; Cannot rule out reverse causality (males earlier CFB and birth weights >4kg)
Friel, 1985; Prospective Cohort Study; Canada; [underlined: Sample Size]:; Baseline N = 110 (50 pre-term, 60 full-term); Analytic N = 110; Attrition = N/A; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 48% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 12% (pre-term) and 47% (full-term) BF at 3mo; At 6mo, 10% (pre-term) and 25% (full-term) given cow’s milk; Pre-term mixed-fed earlier than full-term infants (at 166d vs. 85d) | [underlined: Intervention/Exposure:]; Age of first CFB introduction (NR); Age: 6mo; Assessment Methods:; Diet record, 3d; [underlined: Outcomes:]; Weight; Age: 12mo; Assessment Methods:; Weight: spring balance (pre-term); beam balance (full-term) to 50g *Only weight at 12mo reported in relation to CFB; [underlined: Confounders accounted for:]; SES: X; Sex: X; Birth size: X; Gestational age: X; Other: Maternal age was similar between groups | [underlined: Limitations:]; Cannot determine if inclusion/exclusion criteria were similar across groups; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Did not adjust analyses for potential key confounders (maternal age though groups were similar, education, race/ethnicity, or feeding practices); Only reported outcomes in relation to weight at 12mo and cross-sectional analysis of age of introduction to CFB and length at 3mo
Gaffney, 2012; Prospective Cohort Study; U.S.; [underlined: Sample Size]:; Baseline N = 4902; Analytic N = 691; Attrition = 85.9%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 49.3% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF intensity in late infancy: 52.1% low, 24.3% medium, 23.6% high | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4, 4-6, and >/=6mo; Age: 1, 2, 3, 4, 5, 6, 7, 9, 10, and 12mo; Assessment Methods:; Maternal questionnaire; [underlined: Outcomes:]; Weight; Age: 12mo; Assessment Methods:; Weight: WAZ via maternal-report of weight from recent doctor visit; calculated age and sex-specific z scores by CDC standards; [underlined: Confounders accounted for:]; Education: X; SES: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X (Birth weight); Other: Mother’s smoking status, weight gain in pregnancy, pregravid BMI | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine reliability/validity of outcome assessment and outcome assessors were not blinded due to both feeding and outcome data self-reported by mothers; Did not assess the impact of high loss to follow-up (~40%); Did not adjust analyses for potential confounders (sex, gestational age); Generalizability limited due to sample not being representative (Data not derived from a nationally representative sample, underrepresented minority groups; sample biased toward mothers with more education and higher SES)
Garden, 2012; Prospective Cohort Study; Australia; [underlined: Sample Size]:; Baseline N: 616; Analytic N: 370 (at 3mo, Timing) Analytic N: 298 (at 18mo, Type); Attrition: 40% (3mo); Attrition: 51.6% (18mo); Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 49% female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 40% BF 0-3mo; 16.8% BF 3-6mo; 43.2% BF ≥6mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: ≤3 or >3mo; CFB: solid food ever; Age: 3mo; Assessment Methods:; Questionnaire; [underlined: Outcomes:]; Body composition; Age: birth-11.5y; Assessment Methods:; Body composition: BMI trajectory: calculated in kg/m2 based on measured weight and height (weight, electronic bathroom scale to 1kg; length: portable stadiometer to 1cm); categorized using CDC curves for BMI %tile:; - Normal: tracks at 50^th^; - Early and Persistent: at 75th at 2y crossing to 95th at 11.5y; - Late Increase: tracks at 50th at 2y; crossed to 85th at 8y, and 90th at 11.5y; Measurements made by study nurses at 1, 3, 6, and 9mo; every 6mo from 9mo-5y, at 8y, at 11.5y; WC measured but NR; [underlined: Confounders accounted for:]; Education: X; Sex: X; Race/ethnicity: X; Feeding practices: X; Other: n3 vs. n6 intervention group; parent obesity; smoking | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine whether outcome assessors were blinded; Did not account for high attrition rate/lost to follow-up (40%); Did not adjust for potential key confounders (SES, maternal age, birth size, gestational age)
Gibbs, 2014; Prospective Cohort Study; U.S.; [underlined: Sample Size]:; Baseline N = 10,500; Analytic N = 7,880; Attrition = 25%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 50% Female; [underlined: Race/Ethnicity]:; 50% White; 16% Black, 18% Hispanic, 10% Asian, and 11% other; [underlined: Background Diet]:; 28% BF for ≥3mo, 16% BF ≥6mo, 12% BF 3-5mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4mo or not <4mo; Age: 9mo; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Weight status (Obesity); Age: 24mo; Assessment Methods:; Weight status: risk of obesity, defined as 98th %tile for weight; also reported by WHO and CDC standards and by International Obesity Task Force (IOTF) cut-offs low/high BMI by sex according to measured weight; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X (Birth weight); Gestational age: X; Other: Smoking; Depression, Model 1 or 3: both biological parents in home, sibling size, mother US born, mother’s BMI, twin status, daycare | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Did not account for high attrition rate/lost to follow-up (25%)
Griffiths, 2009; Prospective Cohort Study; United Kingdom; [underlined: Sample Size]:; Baseline N: 18,296; Analytic N: 10,533; Attrition: 42%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 50.1% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 32.1% never BF; 67.9% ever BF; 60.1% BF <4mo; 39.9% BF ≥ 4mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4 vs. ≥4mo; Age: 9mo; Assessment Methods:; Parental interview; [underlined: Outcomes:]; Weight; Age: birth-3y; Assessment Methods:; Weight: conditional weight gain from measured weight (Tanita scales) and z scores by British 1990 standards; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Feeding practices: X; Other: Smoking; Parental BMI; Current child height 3y | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine if outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment; Did not adjust for potential key confounders (maternal age, race/ethnicity, birth size, or gestational age); Retrospective recall; reverse causality; Results were significant before adjustment for current child height z-score (not a key confounder); Race/ethnicity NR ~ appears sample was 100% white
Griffiths, 2010; Prospective Cohort Study; United Kingdom; [underlined: Sample Size]:; Baseline N: 18,296; Analytic N: 11,653; Attrition: ~36%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 50% Female; [underlined: Race/Ethnicity]:; 88% White; 3% Mixed; 2% Indian; 3% Pakistani; 0.8% Bangladeshi; 2% Black; 1% Other; [underlined: Background Diet]:; 29% never BF; 42% BF <4mo; 29% BF ≥ 4mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <17.4 vs. ≥17.4wk; Age: 9mo; Assessment Methods:; Parental interview; [underlined: Outcomes:]; Weight; Age: 3-5y; Assessment Methods:; Weight: rapid weight gain, weight measured via Tanita scales; Measured but NR in relation to CFB: Height: stadiometer; z scores from measures by British 1990 standards; Overweight or Obesity by BMI based on IOTF cut-offs; [underlined: Confounders accounted for:]; Race/ethnicity: X; Gestational age: All full-term; Other: Parental overweight; Smoking; # children in house | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine if outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment; Did not adjust for potential key confounders (education, SES, sex, maternal age, race/ethnicity, feeding practices, birth size, or gestational age)
Grote, 2011; Prospective Cohort Study; U.K./European Union; [underlined: Sample Size]:; Baseline N: 1,090; Analytic N: 687, at 24mo; Attrition: 27%; Power Analysis and Sufficient Sample Size: Powered to detect a 0.6 SD difference at 24mo in any anthropometric measurement in those introduced to CFB early (≤13wk) vs. at 18-21wk.; [underlined: Sex:]; 50% Female; [underlined: Race/Ethnicity]:; 16% Germany; 12% Belgium; 24% Italy; 19% Poland; 29% Spain; [underlined: Background Diet]:; 100% FF (mixed feeding allowed <8wk); Median age of introduction to CFB 19wk; 7% introduced to CFB ≤ 13wk; 97% CFB <6mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: ≤13, 14–17, 18–21, and ≥22wk; Age: 3, 6, 9mo; Assessment Methods:; Food record, 3d, weighed; parental questionnaire; [underlined: Outcomes:]; Body composition; Weight; Length; Age: 3,6, 12, 24mo; 3-24mo; Assessment Methods:; Body composition:; - WLZ, BMI (kg/cm3), BMIZ based on measures;by WHO standards; Weight, length (via digital scale, recumbent length board, or stadiometer): used to calculate WAZ/LAZ and weight velocity (kg/30d or cm/30d) from baseline; [underlined: Confounders accounted for:]; Education: X; Sex: X; Feeding practices: X (Formula group); Other: Country, Birth Order, Age, Partnership Status, Smoking; Maternal BMI; Baseline infant anthropometric values | [underlined: Limitations:]; Cannot determine if outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment (lack of detail provided for single vs. multiple measures); Did not adjust for potential key confounders (SES, maternal age, race/ethnicity, or gestational age); Article notes types of CFB introduced may have had a stronger influence than the timing of CFB on growth; Did not adjust for multiple comparisons
Haschke, 2000; Prospective Cohort Study; Austria, Germany, Spain, France, Greece, UK, Hungary, Croatia, Italy, Ireland, Portugal, Sweden; [underlined: Sample Size]:; Baseline N = 2,245; Analytic N = 1,071; Attrition = 52%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 48.6% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 15.8% WHO group (EBF); 9.1% (Early CFB); 74.9% (controls) | [underlined: Intervention/Exposure:]; Infants were classified into groups based on their feeding patterns:; WHO group: EBF for 4-6mo; Early CFB: Fully BF through 4-6mo + receiving CFB <4mo; Control: Did not meet criteria for the WHO or early solid feeding groups; compared to WHO group; Age of CFB introduction also examined continuously (mo); Age: 0-6mo; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Weight, WAZ, Length, LAZ, BMIZ; Age: 1-12mo; 1-24mo; 1-36mo; 1, 2, 3, 4, 5, 6, 9, 12, 18, 24, 30, or 36mo; Assessment Methods:; Body composition: measured weight/length used to calculate BMI and z-scores; Weight: naked weight on electronic balances, to 1g; Length/Height: (recumbent 1–36mo): Harpenden (UK) stadiometer, to 1mm; standing-height Harpenden stadiometer, to 1mm; [underlined: Confounders accounted for:]; Education: X; Sex: X; Other: Parent height | [underlined: Limitations:]; Cannot determine whether outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment due to lack of details; Did not adjust for potential key confounders (SES, maternal age, race/ethnicity, feeding practices, birth size, or gestational age); Article notes study would have been strengthened by addition of other relevant covariates, such as maternal smoking, family income, etc.
Hawkins, 2009; Prospective Cohort Study; U.K. (England, Wales, Scotland, Northern Ireland); [underlined: Sample Size]:; Baseline N: 18,296; Analytic N: 13,188; Attrition: 27.9%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 50% Female; [underlined: Race/Ethnicity]:; 87% White; 3% Mixed; 2% Indian; 3% Pakistani; 0.9% Bangladeshi; 3% Black; 1% Other; [underlined: Background Diet]:; 30% never BF; 42% BF <4mo; 28% BF ≥4mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4 vs. ≥4mo; Age: 9mo; Assessment Methods:; Parental interview; [underlined: Outcomes:]; Weight status; Age: 0-3y; Assessment Methods:; Weight status: risk of overweight and obesity, categorized based on BMI by IOTF cut-offs; BMI calculated from measure weight (Tanita scales) and height (stadiometer) z scores by British 1990 standards; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X (Birth weight z-scores); Gestational age: X; Other: Smoking; Parental BMI; Maternal hours; Country; Garden access; Food access; Parity; Income; Ward; Marital status | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine if outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment
Heinig, 1993; Prospective Cohort Study; U.S.; DARLING study; [underlined: Sample Size]:; Baseline N: 105; Analytic N: 87 (N: 46 BF; N: 41 FF at 9mo); Attrition: ~17%; Power Analysis and Sufficient Sample Size: NR (N: 56 per group Dewey, 1992); [underlined: Sex:]; 52.8% Female; [underlined: Race/Ethnicity]:; 87% White, non-Hispanic; [underlined: Background Diet]:; All infants were BF or FF and were categorized into groups based on when the child was introduced to solids; Mean age of CFB introduction was later in FF vs. BF infants (23wk vs. 20wk) | [underlined: Intervention/Exposure:]; Age of CFB introduction: BF: <26 vs. ≥26wk; FF: continuously and <20 vs. ≥20wk; CFB: Date when first CFB offered was accepted; Age: 0-26wk (~0-6mo); Assessment Methods:; Food record,4d, weighed; [underlined: Outcomes:]; Weight; Length; Body composition; Age: birth-4mo, 4-6mo, 6-9mo, 9-12mo; 1-18mo; Assessment Methods:; Body composition: WLZ scores by NCHS reference were calcuated from measured weight/height; Weight: velocity(g/month) of mean gain calcuated from measured weight; WAZ; Length: velocity (cm/month) of mean gain calcuated from measured height; LAZ; [underlined: Confounders accounted for:]; Sex: X; Feeding practices: X; Birth size: X (Based on stratified matching of birth weight); Gestational age: All full-term; Other: Growth from 0-4mo; protein intake; energy intake; Stratified matching was used to account for education, SES, maternal age, race/ethnicity | [underlined: Limitations:]; Cannot determine if outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment; Did adjust for potential key confounders (gestational age) Results were partially reported for FF infants by age of introduction to CFB in text (results/discussion) but data not shown; Limited generalizability due to small geographic region
Huh, 2011; Prospective Cohort Study; U.S.; [underlined: Sample Size]:; Baseline N: 1579; Analytic N: 847; Attrition: 46%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 50.3% Female; [underlined: Race/Ethnicity]:; 29.3% non-white; [underlined: Background Diet]:; 67% BF; 33% FF at4mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4, 4-5, and ≥6mo in FF and in BF infants; CFB: 10 solids/food groups, including infant cereal, other starches (teething biscuits, crackers), fruit, vegetables, meat, chicken or turkey, peanut butter, other cow’s milk dairy product; Age: 0-6mo; Assessment Methods:; Maternal questionnaire; [underlined: Outcomes:]; Weight status, Body composition (Adiposity); Weight; Height;; Age: 3y; Assessment Methods:; Weight status: BMI calculated from measured weight/height; BMI z; used for obesity=BMI ≥95th %tile; Body composition: skinfold thickness via calipers; BMI and BMIZ from measures; Weight: Seca scale to 0.1kg; Height: stadiometer to 0.1cm; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Race/ethnicity: X; Birth size: X (Birth weight, birth weight-for-gestational age z-score) (Excluded, no effect); Gestational age: (Excluded, no effect); Other: Early infant-growth 0-4mo; Maternal and Paternal BMI | [underlined: Limitations:]; Groups differed on baseline characteristics and differences were not adjusted for in analyses; Cannot determine if outcome assessors were blinded; Cannot determine reliability/validity of outcome assessment; Did not adjust for potential key confounders (maternal age); Intake regulation may differ in FF vs. BF infants, leading to greater intake of CFB; Wider CI reflecting small number of infants in CFB>6mo group (n=25/279); Limited generalizability
Imai, 2014; Prospective Cohort Study; Iceland; [underlined: Sample Size]:; Baseline N: 250; Analytic N: 154; Attrition: 38.4%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; ~51% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 40% EBF; 7.7% EFF at 5mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: at 5mo; CFB: EBF (N: 62), CFB+BF (N: 57); Age: 5-8mo; Assessment Methods:; Caregiver questionnaire; 24h recall; Food record, weighed 3d; [underlined: Outcomes:]; Weight; Length; Body compsotion; Age: 6-12mo; 12-18mo, 6y; Assessment Methods:; Body composition: BMI from measured height and weight; Weight: scale to 0.1kg; reported as absolute and change in; used for BMI; Length: stadiometer to 0.5cm; reported as absolute and change in; used for BMI; [underlined: Confounders accounted for:]; Education: X; Sex: X; Feeding practices: X (in model); Birth size: X (Birth weight) | [underlined: Limitations:]; Cannot determine if outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment; Did not adjust for potential confounders (SES, maternal age, race/ethnicity, or gestational age); Did not account for high attrition rate (38%); Small sample size (insufficient power); Did not collect information on exact time of introduction of CFB
Johnson, 2014; Prospective Cohort Study; U.K.; [underlined: Sample Size]:; Baseline N: 4860; Analytic N: 4251; Attrition: ~12.5%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 50.3% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 23% never BF, n=1097; 53% BF birth to 4mo,n=2507; 24% BF > 4 mo, n= 1168; ~2% EBF ≥ 4mo, n=95 | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4mo (n=1714), ~5mo (n=1667), ≥6mo (n=1364); Age: 8.2mo; Assessment Methods:; Caregiver questionnaire; [underlined: Outcomes:]; Weight; Age: 6mo, 0-6mo; Assessment Methods:; Weight: Parent report of child health record weight: SDS according to reported weight; SITAR weight trajectory: Tempo was the age of peak weight velocity in wk (higher=delayed tempo); Weight velocity (kg/wk); [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Feeding practices: X; Gestational age: X; Other: Birth order; parity; occupation; smoking; zygosity; child age at baseline | [underlined: Limitations:]; Cannot determine validity/reliability of outcome assessment (parent report); Outcome assessors not blind; Did not adjust for potential confounders (birth size, race/ethnicity); Groups unbalanced (29% in CFB >6mo group)
Kalies, 2005; Prospective Cohort Study; Germany; [underlined: Sample Size]:; Baseline N = 3,036; Analytic N = 2,337; Attrition = 23%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 49% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; Feeding mode during time of observation: 24.4% EBF first 0-1mo, 16.3% BF for 2-3mo, 20.8% BF for 4-5mo, 38.6% BF > or = 6mo. | [underlined: Intervention/Exposure:]; Age of CFB introduction: 1-3mo, 4-6mo, >6mo; Age: 2y; Assessment Methods:; Caregiver questionnaire; [underlined: Outcomes:]; Weight; Age: 24mo; Assessment Methods:; Weight, height: recorded at preventive medical check-ups; reported as risk of elevated weight gain at 24mo; [underlined: Confounders accounted for:]; SES: X; Sex: X; Feeding practices: X; Other: Smoking; maternal BMI; birth order; study center; All full-term | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine if outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment (height and weight non-duplicate at medical check-ups); Did not account for high attrition rate (23%); Did not adjust for potential key confounders (education; maternal age; race/ethnicity, birth size or gestational age); Parent self-reported feeding data; primary objective of study was not timing/type of CFB as such it appears IV/Exposure was used as a confounding in models
Khadivzadeh, 2004; Prospective Cohort Study; Iran; [underlined: Sample Size]:; Baseline N = 200; Analytic N = 193; Attrition = 3.5%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 47% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 100% BF at 4mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: CFB+BF at 4mo vs EBF 4-6mo; Age: 4.5mo; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Weight; Length; Age: 5, 6mo; 4-6mo; Assessment Methods:; Weight: Digital scale; weight and weight gain; Length: Recumbent board; length and length gain; [underlined: Confounders accounted for:]; Sex: X; Maternal age: X; Race/ethnicity: X | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine if outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment; Did not adjust for potential key confounders (education, SES, birth size, gestational age, feeding practices); Degree of antenatal care was significantly higher in exclusively BF vs BF + CFB group but not included as confounder in analysis.
Kramer, 1985; Prospective Cohort Study; Canada; [underlined: Sample Size]:; Baseline N: 462; Analytic N: 347; Attrition: ~25%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 46.1% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; At birth, 58.4% EBF, 72.6% Any BF; At 4mo, 18.8% EBF, 37.2% Any BF; At 6mo, 10.4% EBF, 22.5% Any BF (Kramer, 1985b, based on n: 382 at 6mo) | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous; CFB: cereals and other solids; Age: birth-1y; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Weight; Body composition; Age: 24mo; Assessment Methods:; Body composition:; - BMI: calculated via weight/height2; - Skinfold thickness: sum of triceps, subbscapular, and suprailiac measures via calipers by research staff; Weight: measured at home-visit by research staff; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Feeding practices: X (duration of BF, step-wise); Gestational age: All full-term | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine validity/reliability of outcome assessment (insufficient detail); Did not account for high rate of attrition (>20%) ; Did not adjust for potential key confounders (race/ethnicity, birth size, gestational age)
Kramer, 1985b; Prospective Cohort Study; Canada; [underlined: Sample Size]:; Baseline N: 462; Analytic N: 382; Attrition: ~17%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 46.1% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; At birth, 58.4% EBF, 72.6% Any BF; At 4mo, 18.8% EBF, 37.2% Any BF; At 6mo, 10.4% EBF, 22.5% Any BF | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous; CFB: cereals and other solids; Age: 0-4mo; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Body composition; Weight; Age: 6mo, 12mo; Assessment Methods:; Body composition:; - BMI: calculated via weight/height2; - Skinfold thickness: sum of triceps, subbscapular, and suprailiac measures via calipers by research staff; Weight: measured at home-visit by research staff; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Feeding practices: X; Birth size: X (birth weight); Gestational age: All full-term | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine validity/reliability of outcome assessment (insufficient detail); Did not adjust for potential key confounders (race/ethnicity, birth size, gestational age); Lack of detail on outcome measurements
Kramer, 2004; Prospective Cohort Study; Belarus; [underlined: Sample Size]:; Baseline N: 17,601; Analytic N: 17,046; Attrition: 3%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; NR; 100% were BF at birth | [underlined: Intervention/Exposure:]; Age of CFB introduction: intake (any vs. none) of CFB at the start of the respective growth interval; CFB: cereals, other solids, and juices; Age: 0-12mo; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Body composition; Weight; Length; HC; Age: 1-3mo; 3-6mo; 6-9mo; 9-12mo; Assessment Methods:; Body composition: WLZ based on CDC/WHO, 2000; Weight: NR; used to calculate WAZ; Length: NR; used to calculate LAZ; HC: NR; [underlined: Confounders accounted for:]; Education: X; Birth size: X (All with birth weight >2.5kg); Gestational age: All full-term; Other: Anthropometric outcome at current time (WAZ, LAZ, WLZ, HC), geographic region, urbanicity, hospital | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment (unstandardardized); Did not adjust for potential key confounders (SES, sex, maternal age, race/ethnicity though participants were from RCT); Cereals consumed may not be generalizable; Only 1.2% of infants were consuming cereals at 3mo; Cannot rule out reverse causality, residual confounding, and selection bias; Trial promoted breast-feeding; Outcome assessment was unstandardized (various methods used; not primary outcome of original RCT)
Kuperberg, 2006; Prospective Cohort Study; Canada; [underlined: Sample Size]:; Baseline N: 102; Analytic N: 71; Attrition: 30%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 49% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 75% initiated BF; 57.1% CFB by 4mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous; Dichotomous (y/n) <4mo; CFB: solids, and cow’s milk; Age: 48mo; Assessment Methods:; Maternal questionnaire; 24hr recall; [underlined: Outcomes:]; Weight status; Age: 48mo; Assessment Methods:; Weight status: risk of overweight, based on BMI ≥ 85th %tile from measured length/height and weight. Weight at 3 and 18mo measured via portable infant scale; at 33 and 48mo, electronic scale.; Length: at 3 and 18mo measured via pediatric length board; height at 33 and 48mo, measured via microtoise modified tape measure; [underlined: Confounders accounted for:]; Other: NR | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine whether outcome assessors were blinded; Did not account for high rate of attrition to 48mo; Did not adjust for potential key confounders (education, SES, sex, maternal age, race/ethnicity, feeding practices, birth size, or gestational age); Mother’s health information not available at 3mo; Limited IV/Exposure assessment to maternal self-report and one, 24hr recall; Lack of relevant data
Lande, 2005; Prospective Cohort Study; Norway; [underlined: Sample Size]:; Baseline N: 1934 (3000 mailed; 1934 returned at 12mo); Analytic N: 1441; Attrition: ~25%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 47% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; NR | [underlined: Intervention/Exposure:]; Age of CFB introduction: ≤4, 4-5, >5mo; Age: 6mo; 12mo; Assessment Methods:; Parental FFQ; [underlined: Outcomes:]; Body composition; Age: 12mo; Assessment Methods:; Body composition:; - BMI: calculated based on height and weight measured by health-care personnel; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Feeding practices: X; Birth size: X; Gestational age: All full-term; Other: Smoking; Birth order | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment; Cannot determine if length of follow-up differed between groups; Did not adjust analyses for potential key confounders (race/ethnicity, and gestational age); Not all relevant data was shown/reported;; Note: daily/weekly use of CFB at 6mo was collected but only compared against PI at birth; or in univariate analyses; and not against BMI at 12mo; univariate analyses showed significant effect of age of CFB intro
Lauver, 1981; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N: 202; Analytic N: 77; Attrition: 62%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; 47% Black; 48% White; 5% Other; [underlined: Background Diet]:; 25% BF; 75% formula; 12% consumed CM by 6mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: ≤5 or >5mo; CFB: Beikost/solids; Non-compliant were given CFB ≤5mo; compliant were given CFB >5mo; Age: 5mo; Assessment Methods:; Caregiver interview; [underlined: Outcomes:]; Weight; Length; Age: 6mo; Assessment Methods:; Weight and length recorded at clinic visits; [underlined: Confounders accounted for:]; Maternal age: X; Feeding practices: X; Birth size: X | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine adherence to protocols across groups; Unintended exposures not accounted for (differences between groups in BF and cow’s milk); Cannot determine whether investigators were blinded; Cannot determine validity/reliability of outcome assessment; Did not adjust for potential key confounders (education, SES, sex, or gestational age); Adequacy of statistical methods was insufficient
Layte, 2014; Prospective Cohort Study; Ireland; [underlined: Sample Size]:; Baseline N: 16,136; Analytic N: 11,134; Attrition: 31%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 49% Female; [underlined: Race/Ethnicity]:; 86.3% Irish; 1.8% UK;; 6.6% EU; 2.4% African; 2.8% Other; [underlined: Background Diet]:; 57.1% never BF; 4.3% BF<3mo; 5.6% BF<6mo; 8.8% BF 6+mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4mo, <5mo, <6mo, ≥6mo; Age: 9mo; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Weight status; Weight; Age: 0-9mo, 3y; Assessment Methods:; Weight status: risk of obesity based on BMI , calculated from measured height/weight by IOTF thresholds; Weight: rapid gain calculated by measured weight on Seca scale to 0.5kg and length/height measured by height stick and indexed by IOTF; [underlined: Confounders accounted for:]; SES: X; Sex: X; Maternal age: X; Feeding practices: X (BF in model); Birth size: X (Birth weight); Gestational age: X; Other: Multiples; Birth order; Weight gain in pregnancy | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment; Did not adjust analyses for potential key confounders (education, race/ethnicity, and feeding practices though part of modeling)
Leary, 2015; Prospective Cohort Study; United Kingdom; [underlined: Sample Size]:; Baseline N: 5,112; Analytic N: 4,750; Attrition: 7%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 52.3% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 36.4% EBF; 49.5% PBF; 14.1% no BF | [underlined: Intervention/Exposure:]; Age of CFB introduction: ≤2, 3, ≥4mo; Age: 6mo; Assessment Methods:; Maternal questionnaire; [underlined: Outcomes:]; Body composition; Age: 15y; Assessment Methods:; Body composition: FM, lean mass via DXA; BMI: not reported in relation to CFB; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Feeding practices: X; Birth size: X; Gestational age: X; Other: Current age; Maternal height; Parity | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Did not adjust for potential key confounders (race/ethnicity)
Makela, 2014; Prospective Cohort Study; Finland; [underlined: Sample Size]:; Baseline N: 1797; Analytic N: 848; Attrition: 52%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 48% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; EBF duration: 2.6mo, BF duration: 8.6mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous, mo; Categorical <4, 4-6, >6mo; CFB: vegetables, fruits, grains, meat, fish and dairy categories not defined; Age: birth-12mo; Assessment Methods:; Food diaries, collected in real-time; [underlined: Outcomes:]; Weight status; Weight; Age: birth-24mo; at 24mo; Assessment Methods:; Weight status: risk of overweight or obesity based on Finnish age- and sex-specific growth references; Weight: Measured by study personnel, to nearest 0.1kg; [underlined: Confounders accounted for:]; Sex: X; Feeding practices: X (BF, EBF duration); Birth size: X; Gestational age: X; Other: Gestational weight gain, maternal pre-pregnancy BMI | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., single vs multiple growth measures); Cannot determine how timing of introduction of individual food groups was analyzed; did not report outcomes for length or BMI; Did not account for high loss to follow-up (~52%); Did not adjust for potential key confounders (education, SES, maternal age, race/ethnicity)
Moss, 2014; Prospective cohort study; U.S.; [underlined: Sample Size]:; Baseline N = 9550; Analytic N = 7200 at 2y, 6950 at 4y; Attrition = 25% at 2y, 27% at 4y; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; Ever BF: 70%; Age CFB introduced: 24% <4mo, 50% 4-5mo, 26% >6mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4, 4-5, ≥6mo; Age: 9mo; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Weight status; Age: 2y, 4y; Assessment Methods:; Weight status: BMI percentile calculated using measured height/weight; classified as healthy weight (<85^th^), overweight (85-94^th^), or obese (≥95^th^); [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X (Birth weight) | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; cannot determine whether outcome assessors were blinded; Did not account for high loss to follow-up (>20%); Did not adjust for potential key confounders (gestational age)
Neutzling, 2009; Prospective Cohort Study; Brazil; [underlined: Sample Size]:; Baseline N: 1460; Analytic N: 1204; Attrition = 18%; Power Analysis and Sufficient Sample Size: Yes, N=1,204 (to detect statistically significant relative risks of 0.7); [underlined: Sex:]; 50% Female; [underlined: Race/Ethnicity]:; 71% White, 29% Black or mixed skin color; [underlined: Background Diet]:; BF duration: 18% >12mo; EBF: 15% >4mo; Ever BF: 96%; Age of CFB introduction: 49% <4mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4, >4mo; Age: 6, 12mo; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Weight status; Age: 11y; Assessment Methods:; Weight status: risk of overweight (>85th percentile for BMI), and obesity (>85th percentile for BMI, >90th percentile for skinfolds); BMI percentile calculated using measured weight, height; triceps/subscapular skinfolds measured with calipers; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Race/ethnicity: X; Feeding practices: X; Birth size: X; Other: Smoking, maternal pregestational BMI | [underlined: Limitations:]; Cannot determine whether outcome assessors were blinded; Did not adjust for potential key confounders (maternal age, gestational age)
Pan, 2016; Prospective Cohort Study; U.S; [underlined: Sample Size]:; Baseline N: 1542; Analytic N: 1189; Attrition: 22.9%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 50% Female; [underlined: Race/Ethnicity]:; 88% White non-Hispanic, 3.4% Black non-Hispanic, 4.8% Hispanic, 3.9% Other non-Hispanic; [underlined: Background Diet]:; BF duration: 48.6% <6 mo ; 51.4% ≥6mo | [underlined: Intervention/Exposure:]; Age of CFB introduction (<4mo, Y/N); Age of SSB (juice drinks, soft drinks, soda, sweet tea, Kool-Aid) introduction: never, <6mo, ≥ 6mo; Age: 10-12mo; Assessment Methods:; Caregiver questionnaire; [underlined: Outcomes:]; Weight status; Age: 6y; Assessment Methods:; Obesity: based on BMI-for-age ≥95th %tile, calculated from maternal-report of weight and height taken with scale and tape; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X; Gestational age:; Other: age at CFB introduction; pregnancy weight status | [underlined: Limitations:]; Cannot determine reliability/validity of outcome assessment and outcome assessors were not blinded due to both feeding and outcome data self-reported by mothers; Did not assess the impact of high loss to follow-up (~22.9%); Did not adjust analyses for potential confounders (gestational age); Limited generalizability due to sample not being representative (Data not derived from a nationally representative sample, underrepresented minority groups; sample biased toward mothers with more education and higher SES)
Piwoz, 1996; Prospective Cohort Study; Peru; [underlined: Sample Size]:; Baseline N: 156; Analytic N: 140; Attrition: 11%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; EBF to 4mo: 21%, BF/FF at 4mo: 13%; Age of introduction of CFB: 61% by 4mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4 (BF/FF+CFB), >4mo (BF/FF); Age: 4mo; Assessment Methods:; Caregiver questionnaire; [underlined: Outcomes:]; Weight; Age: birth-3mo; >3mo; Assessment Methods:; Weight: Measured by study personnel in duplicate, to nearest 100g; [underlined: Confounders accounted for:]; Birth size: X (All with birth weight >2.5kg) | [underlined: Limitations:]; Groups differed at baseline on key characteristics that were not adjusted for in analyses (birthweight, age of formula and CFB introduction, calorie intake, diarrhea and fever prevalence); Cannot determine whether outcome assessors were blinded; Did not adjust for key confounders (sex, gestational age, race/ethnicity); Data and statistical comparisons reported in figures is not described (mean values, P-values, etc.); Limited generalizability of population due to time of data collection; Cannot rule out reverse causality (BF/FF practices during age of outcome)
Quandt, 1984; Prospective Cohort Study; U.S.; [underlined: Sample Size]:; Baseline N: 91; Analytic N: 45; Attrition: 50%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 47% Female; [underlined: Race/Ethnicity]:; 100% White; [underlined: Background Diet]:; EBF at baseline: 100%; Age of CFB introduction: ~120d (36-178d) | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4, >4mo; Age: 2wk to 6mo; Assessment Methods:; Food diaries, collected in real-time; [underlined: Outcomes:]; Body composition; Weight; Length; Age: 1, 2, 3, 4, 5, 6mo; Assessment Methods:; Body composition: WLZ calculated from measures; Weight and Length (recumbent): Measured by study personnel using standard anthropometric techniques; [underlined: Confounders accounted for:]; None | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., single vs multiple growth measures); Did not account for high loss to follow-up (50%); Did not adjust for potential key confounders (education, SES, sex, maternal age, race/ethnicity, feeding practices, birth size, gestational age); Small sample size; Cannot rule out reverse-causality (tming of CFB during outcome assessment)
Reilly, 2005; Prospective Cohort Study; United Kingdom; [underlined: Sample Size]:; Baseline N: 13971; Analytic N: 5493; Attrition: 61%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 49% Female; [underlined: Race/Ethnicity]:; 86% White; [underlined: Background Diet]:; EBF at 2mo: 28%; Never BF: 15% | [underlined: Intervention/Exposure:]; Age of CFB introduction: <1, 1-2, 2-3, 3-4, 4-6, >6mo; Age: 6mo; Assessment Methods:; Parent questionnaire; [underlined: Outcomes:]; Weight status; Age: 7y; Assessment Methods:; Weight status: risk of obesity (BMI ≥95th %tile); BMI calculated using measured weight, height; [underlined: Confounders accounted for:]; Education: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X; Gestational age: X; Other: Energy intake at 3y, parity, maternal smoking, season of birth, # of fetuses, parental obesity, siblings, time spent watching tv and in the | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., single vs multiple growth measures); Did not account for high loss to follow-up (61%); Did not adjust for potential key confounders (SES)
Robinson, 2009; Prospective Cohort Study; U.K.; [underlined: Sample Size]:; Baseline N: 1195; Analytic N: 536; Attrition: 55%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 47% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; Never BF: 12.5%; BF for 6mo: 20%; Age of introduction to CFB: 76% by 4mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: Not defined; Age: 6mo, 12mo; Assessment Methods:; FFQ; maternal interview; [underlined: Outcomes:]; Body composition; Age: 4y; Assessment Methods:; Body composition:; - BMI: Calculated using measured height, weight; - Lean mass: Whole-body DXA measurement; Lean mass index: lean mass divided by height^2^;; - Fat mass (FM): Whole-body DXA measurement; Fat mass index (FMI): FM divided by height^2^; [underlined: Confounders accounted for:]; SES: X; Maternal age: X; Feeding practices: X; Birth size: X; Other: Maternal BMI, maternal height, smoking in late pregnancy | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of some outcome measures (i.e., single vs multiple height, weight measures); Did not define age of introduction of CFB variable; Did not account for high loss to follow-up (55%); Did not adjust for potential key confounders (education, sex, race/ethnicity, gestational age)
Rossiter, 2013; Prospective Cohort Study; Canada; [underlined: Sample Size]:; Baseline N: 546; Analytic N: 377; Attrition: 31%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 43% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF initiated: 75%; BF at 3mo: 44%; Age of CFB introduction: 50% <4mo, 10% <2mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4, >4mo; Age: 3, 18, 33, and 48mo; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Weight status; Age: 4y; Assessment Methods:; Weight status: prevalance of overweight/obesity vs. normal/under weight with overweight classified as BMI≥85th percentile, and obesity as BMI≥95th percentile; BMI calculated using measured (duplicate) weight, height; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Feeding practices: X; Birth size: X; Gestational age:; Other: Maternal birthplace, smoking, siblings, marital status, number of people in home, parental classes, maternal weight | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Did not account for high loss to follow-up (31%); Did not adjust for potential key confounders (race/ethnicity, gestational age)
Salmenpera, 1985; Prospective Cohort Study; Finland; [underlined: Sample Size]:; Baseline N: 198; Analytic N: at 6-9mo, N: 113 (FF+CFB N: 32; EBF N:36; BF+CFB N:45); Analytic N: at 9-12mo, N: 84 (FF+CFB N: 32; EBF N:7; BF+CFB N:45); Attrition: at 6-9mo, 42%; at 9-12mo, 58%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 53% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF at 6mo: 59%; Age of CFB introduction: 42% between 4-6mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: BF+CFB (6-9mo, or 9-12mo, N:45) vs. EBF (6-9mo, N:36 or 9-12mo, N: 7); *Article “comparison group” of FF+CFB <3.5mo of age is not included here; Age: NR; Assessment Methods:; NR; [underlined: Outcomes:]; Weight; Length; Age: 6-12mo; Assessment Methods:; Weight: velocity from weight measured by study personnel to nearest 5g; Length: velocity from recumbent length measured with length board by study personnel to nearest 1mm; [underlined: Confounders accounted for:]; Gestational age: X | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome asssessment (i.e., single vs multiple growth measures); limited information provided regarding infant feeding measures; Did not account for high loss to follow-up (>40%); Did not adjust for key confounders (education, SES, sex, maternal age, race/ethnicity, feeding practices, birth size); Data and statistical comparisons reported in tables/figures for other relevant outcomes and sub-groups were not described (e.g., head circumference and skinfold comparisons not shown for BF+CFB vs. EBF); Article notes potential for reverse causality (faster growing infants had earlier timing of CFB/greater infant demand)
Santorelli, 2014; Prospective Cohort Study; United Kingdom; [underlined: Sample Size]:; Baseline N: 1735; Analytic N: 1327; Attrition: 24%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; 38% White, 49% Pakistani, 7% South Asian, 6% Other; [underlined: Background Diet]:; BF after CFB introduction: 32%; Age of CFB introduction: 10% <17wk | [underlined: Intervention/Exposure:]; Age of CFB introduction: <17, >17wk; CFB: sweetened foods a/o drinks; Age: 6, 12mo; Assessment Methods:; Maternal questionnaire; [underlined: Outcomes:]; Body composition; Age: 3y; Assessment Methods:; Body composition: BMIZ: calculated using measured height, weight and converted into age- and sex-adjusted z-scores based on WHO, 2006 growth standards; [underlined: Confounders accounted for:]; Education: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X; Gestational age: X; Other: Marital status, smoking during pregnancy, maternal BMI, delivery mode | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome measures (i.e., single vs multiple growth measures); Did not account for high loss to follow-up (24%); Did not adjust for potential key confounders (SES)
Schack-Nielsen, 2010; Prospective Cohort Study; Denmark; [underlined: Sample Size]:; Baseline N: 8129; Analytic N: 5068; Attrition: 39%; Power Analysis/Sample Size Calculation: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF duration: 3.5mo; BF <2wk: 18%; Age of CFB introduction: 3.8mo | [underlined: Intervention/Exposure:]; Age of introduction to CFB: Continuous, mo; Categorical, ≥4 vs <4mo; CFB: spoon-feeding, vegetables, eggs, meat, firm food; Age: 1y; Assessment Methods:; Maternal questionnaire; [underlined: Outcomes:]; Weight status; Body composition; WC; Age: 1-42y; Assessment Methods:; Weight status: risk of overweight based on BMI ≥25 using self-reported height and weight at 42y; Body composition: BMI calculated using height, weight measured by study personnel at 1, 3, and 6y; school records at 7-14y; self-reported at 2-34y, 42y; WC: Self-reported at 42y via mailed questionnaire and tape measure; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Race/ethnicity:; Feeding practices: X; Birth size: X (Birth weight); Gestational age: X; Other: Prepregnancy BMI, gestational weight gain, smoking during pregnancy, marital status, weight at 1y | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Outcome assessors were not blinded at 20-34y, 42y; Did not use valid/reliable measures to assess outcomes (weight was self-reported at 20-34y and 42y); Did not account for high loss to follow-up (39%); Did not adjust for potential key confounders (race/ethnicity); Not all variables were analyzed in relation to all outcomes, and data from figures not adequately described; Limited generalizability (CFB practices in 1959-1960)
Seach, 2010; Prospective Cohort Study; Australia; [underlined: Sample Size]:; Baseline N: 620; Analytic N: 307; Attrition: 50%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; 99% White; [underlined: Background Diet]:; Ever BF: 94%; EBF duration: 15wk; BF duration: 48wk; Age of CFB introduction: 20wk (6% >6mo) | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous, wk; Age: 0-64wk (weekly), 78wk, 2y; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Weight status; Age: 10y; Assessment Methods:; Weight status: BMI calculated using measured height, weight (methods NR); classified into age- and sex-standardized BMI categories (normal weight, overweight and obese); overweight and obese were combined to create a binary outcome variable of an ‘above healthy’ BMI vs. ‘healthy’; [underlined: Confounders accounted for:]; Education: X; SES: X; Race/ethnicity: X; Feeding practices: X; Birth size: X; Other: Parental smoking, childcare | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome measures (i.e., single vs multiple growth measures); Did not account for high loss to follow-up (50%); Did not adjust for potential key confounders (sex, maternal age, gestational age)
van Rossem, 2013; Prospective Cohort Study; The Netherlands; [underlined: Sample Size]:; Baseline N: 7295; Analytic N: 3184; Attrition: 56%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; 68% Dutch, 12% Other Western, 21% Non-Western; [underlined: Background Diet]:; BF at 2mo: 69%, BF at 6mo: 33%; Age of CFB introduction: 5% 0-3mo, 57% 3-6mo, 38% >6mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: 0-3, 3-6, >6mo; Age: 12mo; Assessment Methods:; Maternal questionnaire; [underlined: Outcomes:]; Body composition; Age: 12-45mo; Assessment Methods:; Body composition:; - WLZ/WHZ: change in weight-for-length/height (kg/cm gain in length) z score according to Dutch reference; weight (SECA scale), length/height (supine/stadiometer) were measured by study personnel; [underlined: Confounders accounted for:]; Education: X; Race/ethnicity: X; Feeding practices: X; Gestational age: X (All >37wk); Other: Smoking during pregnancy, maternal BMI, history of allergy or hospital admission in the first year of life | [underlined: Limitations:]; Birth weight differed between timing of CFB groups, and was not adjusted for in analyses (all subjects were normal birth weight); Cannot determine if outcome assessors were blinded; Cannot determine the validity/reliability of outcome measures (i.e., single vs multiple measures); Did not adjust for several potential key confounders (SES, sex, maternal age, birth size); Adequacy of statistical methods insufficient (statistical comparisons between different timing of CFB introduction were not clearly made in tables, figures, or text); Infants introduced to CFB earlier had higher WLZ before CFB introduction; confidence intervals in tables indicate significance but comparisons were not clear
Victora, 1998; Prospective Cohort Study; Brazil; [underlined: Sample Size]:; Baseline N: 655; Analytic N: 627; Attrition: 4%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 51% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF: 100% | [underlined: Intervention/Exposure:]; Age of CFB introduction: <3, >3mo; Age: 1, 3, 6mo; Assessment Methods:; 24-hr recall; [underlined: Outcomes:]; Body composition; Weight; Length; Age: 3-6mo; Assessment Methods:; Body composition: ponderal index derived from weight divided by length^3^; Weight: Measured by study personnel, to nearest 100g; Length: Measured by study personnel, recumbent; [underlined: Confounders accounted for:]; Education: X; SES: X; Other: Housing quality, crowding index, number of children <5y in house | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., single vs multiple measures); Did not adjust for potential key confounders (sex, maternal age, race/ethnicity, feeding practices, birth size, gestational age); Limited generalizability due to study setting (lower HDI at the time of data collection)
Villalpando, 2000; Prospective Cohort Study; Mexico; [underlined: Sample Size]:; Baseline N: 216; Analytic N: 170; Attrition: 21%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF at birth: 90%; BF at 6mo: 25%; Age of CFB introduction: 86% by 4mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: 15d intervals from 0-6mo, Continuous; Age: 0-6mo; Assessment Methods:; Maternal interview, every 15d; [underlined: Outcomes:]; Weight; Length; Age: 0-6mo; Assessment Methods:; Weight: Measured by study personnel with an electronic balance; Length: Measured by study personnel using a length board; [underlined: Confounders accounted for:]; Feeding practices: X; Birth size: X (All with birth weight 2500-4000g; Birth BMI); Gestational age: X (All full term); Other: Age, episodes of infection | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., insufficient detail regarding single vs multiple measures); Did not account for high loss to follow-up (21%); Did not adjust for potential key confounders (education, SES, sex, maternal age, race/ethnicity); Limited generalizability (sample from slum population); Cannot rule out reverse causaliy (timing of CFB during outcome assessment)
Warrington, 1988; Prospective Cohort Study; U.K.; [underlined: Sample Size]:; Baseline N: 109; Analytic N: 78; Attrition: 28%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; 50% White, 50% Asian; [underlined: Background Diet]:; EBF for 12wk+: 5%; FF from birth: 40%; Age of CFB introduction: 46% <12wk | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous, wk; Age: 3, 6, 9 12, and 24mo; Assessment Methods:; Food records, 3d, weighed; [underlined: Outcomes:]; Weight; Age: 1y, 2y; Assessment Methods:; Weight: Measured by study personnel; [underlined: Confounders accounted for:]; Race/ethnicity: X | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine if adherence was similar across study groups; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (methods not described); Did not account for high loss to follow-up (28%); Did not adjust for potential key confounders (Education, SES, sex, maternal age, feeding practices, birth size, gestational age); Adequacy of statistical methods insufficient (did not provide data table or statistics to accompany results reported via figure and text)
Wells, 1998; Prospective Cohort Study; U.K.; [underlined: Sample Size]:; Baseline N: 50; Analytic N: 20; Attrition: 60%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF and FF | [underlined: Intervention/Exposure:]; Age of CFB introduction: <12, >12wk; Age: 12wk; Assessment Methods:; Food records, 1d, weighed; [underlined: Outcomes:]; Body composition (Adiposity); Weight; Height; Age: 2-3.5y; Assessment Methods:; Body composition:; - FM, FFM: Calculated using total body water and weight; - Skinfold thickness (triceps, subscapular): Measured by study personnel; Weight: Measured by study personnel; Height: Measured by study personnel; [underlined: Confounders accounted for:]; Feeding practices: X (energy intake, milk volume intake); Gestational age: X (all full term); Other: Child age, infant soothability score | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., single vs multiple measures); Length of follow-up ranged from 2-3.5y; Did not account for high loss to follow-up (60%); Did not adjust for potential key confounders (education, SES, sex, maternal age, birth size); Did not provide data table to accompany all results reported in text
Wen, 2014b; Prospective Cohort Study; Australia; [underlined: Sample Size]:; Baseline N: 330; Analytic N: 242; Attrition: 27%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 54% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; Duration of BF: 5.82mo; Ever BF: 97%; Age of CFB introduction: 8% <2mo, 28% 3-5mo, 64% >6mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <2, 3-5, >6mo; Age: 6mo; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Weight status; Body composition; Age: 2y; Assessment Methods:; Weight status: Overweight classified as BMI>25kg/m2, obese as BMI>30kg/m2; Body composition: BMI calculated using measured (duplicate) weight, length; [underlined: Confounders accounted for:]; SES: X (Household income; employment status); Sex: X; Education: X; Feeding practices: X; Birth size: X (birth weight); Other: Marital status, tv time, mothers BMI and weight status, mothers county of birth; age of starting tummy time; using bottle at 1y; outdor activity time; food for reward; dietary intake at 2y; maternal age | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Did not account for high loss to follow-up (27%); Did not adjust for potential key confounders (race/ethnicity, gestational age) Limited generalizability (sample was “very disadvantaged”)
WHO, 2002; Prospective Cohort Study; China, India, Guatemala, Nigeria, Chile, Sweden, Australia; [underlined: Sample Size]:; Baseline N: NR; Analytic N: 1252; Attrition: CD; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 45% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF: 100% | [underlined: Intervention/Exposure:]; Age of CFB introduction: 1-8, 9-16, 25-32wk vs 17-24wk; Age: 0-32wk; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Weight; Length; Age: 8wk (midpoint of 1-16wk), 24wk (midpoint of 17-32wk); Assessment Methods:; Weight: Measured by study personnel; Length: Measured by study personnel; [underlined: Confounders accounted for:]; Education: X; Sex: X; Maternal age: X; Feeding practices: X (BF duration, food given to infant before BF, access of infant to breast, BF per day); Birth size: X (all with birth weight >2500g); Gestational age: X; Other: maternal surgery, number of previous births, maternal health | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine loss to follow-up, baseline sample size not reported; Did not adjust for potential key confounders (SES, race/ethnicity); Statistical analyses were difficult to interpret (i.e., in several cases, the exposure of CFB introduction occurred after the time point at which the outcome was measured); Results showed small differences in growth based on timing of CFB introduction that were statistically significant but probably not biologically important; Limited generalizability (exclusively enrolled high SES)
Wolman, 1984; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N: 262; Analytic N: 164; Attrition: 37%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF 1-12 wk: 16%; BF >13wk: 5%; Age of introduction to CFB: 89% <3mo; 65% before 1mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <12, >13wk; Age: 0-24mo; Assessment Methods:; Parent questionnaire; [underlined: Outcomes:]; Body composition (BMI); Weight; Height; Age: 4-6y; Assessment Methods:; Body composition:; - BMI calculated using height, weight taken from medical records; Weight: Taken from medical records; Height: Taken from medical records; [underlined: Confounders accounted for:]; None | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Did not use valid/reliable measures to assess outcomes (growth measures taken from medical records); Cannot determine whether length of follow-up was similar across groups (follow-up age ranged from 4-6y); Did not account for high loss to follow-up (37%); Did not adjust for potential key confounders (SES, sex, education, maternal age, race/ethnicity, feeding practices, birth size, gestational age)
Woo, 2013; Prospective Cohort Study; United States, Mexico, China; [underlined: Sample Size]:; Baseline N: 365; Analytic N: 285; Attrition: 22%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; 33% US, 33% Mexican, 33% Chinese; [underlined: Background Diet]:; EBF duration: 5wk in China, 14wk in US, 7wk in Mexico; BF duration: 37wk in China, 50wk in US, 52wk in Mexico; Age of CFB introduction: 18wk in China, 23wk in US, 25wk in Mexican | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous, mo; Age: 0-1y; Assessment Methods:; 24-hr food frequency recall of 21 food items, weekly; [underlined: Outcomes:]; Body composition (BMI); Weight; Length; Age: 1y; Assessment Methods:; Body composition:; - BMI calculated using measured height, weight; Weight: Measured by study personnel in duplicate; Length: Measured by study personnel in duplicate, supine; [underlined: Confounders accounted for:]; Education: X; Sex: X; Maternal age: X; Feeding practices: X; Birth size: X; Gestational age: X (All >37wk); Other: Prepregnancy BMI, gestational weight gain, gestational diabetes, type of delivery, cohort site | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Did not account for high loss to follow-up (22%); Did not adjust for key confounders (SES, race/ethnicity)
Worobey, 2009; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N: 242; Analytic N: 96; Attrition: 60%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 51% Female; [underlined: Race/Ethnicity]:; 24% Black, 76% Hispanic; [underlined: Background Diet]:; FF: 100%; Age of CFB introduction: 4.23mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous, mo; Age: 3, 6, 12mo; Assessment Methods:; Food record; [underlined: Outcomes:]; Weight; Age: 3-6mo; Assessment Methods:; Weight: Measured by study personnel trained in reliable measurement; [underlined: Confounders accounted for:]; Education: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X (# feeds per day); Birth size: X; Other: Maternal BMI, weight and length gain from 0-3mo, maternal sensitivity to infant signals, country of origin, prepregnancy BMI, gestational weight gain | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Did not account for high loss to follow-up (60%); Did not adjust for potential key confounders (SES, gestational age)
Worobey, 2014; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N: 242; Analytic N: 154; Attrition: 36%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; 24% Black, 54% Mexican, 25% other Latino; [underlined: Background Diet]:; FF: 100% | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous, mo; Age: 3, 6, 12mo; Assessment Methods:; Food record; [underlined: Outcomes:]; Weight; Age: 3-6mo; Assessment Methods:; Weight: Measured by study personnel trained in reliable measurement; [underlined: Confounders accounted for:]; Feeding practices: X (# of feeds at 3mo); Birth size: X; Other: Maternal BMI, # of cries at 3mo, # of cry-feeds at 3mo, infant weight at 3mo, total sleep at 3mo | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Did not account for high loss to follow-up (36%); Did not adjust for potential key confounders (education, SES, sex, maternal age, race/ethnicity, gestational age)
Wilson, 1998; Prospective Cohort Study; U.K.; [underlined: Sample Size]:; Baseline N: 674; Analytic N: 545; Attrition: 19%; Sample Size Calculation: NR; [underlined: Sex:]; 54% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; EBF at 15wk: 26%, partial BF at 15wk: 37%, formula fed at 15wk: 37% | [underlined: Intervention/Exposure:]; Age of CFB introduction: <15, >15wk; Age: 0-2y; Assessment Methods:; Parent questionnaire; [underlined: Outcomes:]; Weight, height, BMI, % body fat; Age: 7y; Assessment Methods:; Body composition:; - BMI calculated using measured height, weight; - % body fat calculated based on bioelectrical impedance (and skinfold thickness NR); Weight: Measured by study personnel; Height: Measured by study personnel; [underlined: Confounders accounted for:]; SES: X; Sex: X; Feeding practices: x; Birth size: X (Birth weight); Other: Height, maternal height, weight at first solids | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., single vs multiple measures); Did not adjust for potential key confounders (education, race/ethnicity, gestational age) Article states skinfold thickness measures were taken but data NR
Yeung, 1981; Prospective Cohort Study; Canada; [underlined: Sample Size]:; Baseline N: 403; Analytic N: 316; Attrition: 22%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF: 56% at 1mo, 39% at 3mo, 26% at 5mo, 21% at 6mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <2, >2mo; Age: 1, 3, 5, 6, 7, 8, 10, 12, 15, 18mo; Assessment Methods:; Food record, 4d; [underlined: Outcomes:]; Body composition; Age: 6mo; Assessment Methods:; Body composition:; - Skinfold thickness sum of triceps and subscapular skinfolds measured by study personnel; [underlined: Confounders accounted for:]; Gestational age: X (All full term) | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., single vs multiple measures); Did not account for high loss to follow-up (22%); Did not adjust for ptoential key confounders (education, SES, sex, maternal age, race/ethnicity, feeding practices, birth size)
Zheng, 2015; Prospective Cohort Study; China; [underlined: Sample Size]:; Baseline N: 90066; Analytic N: 40510; Attrition: 55%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 48% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; Ever BF: 93% | [underlined: Intervention/Exposure:]; Age of CFB introduction: ≤3, 4-6, >6mo; CFB: fish liver oil, rice cereal/porridge, egg yolk, fish paste, liver paste, tofu, animal blood, bread/steamed bun/fine dried noodle, ground meat/soy product, and pureed noodle/cookies; Age: 1, 3, 6mo; Assessment Methods:; Maternal interview; [underlined: Outcomes:]; Weight status; Body composition; Age: 4-5y; Assessment Methods:; Weight status: Obesity defined as BMI z-score>2SD, overweight defined as between 1-2SD; Body composition: BMI calculated using self-reported weight, height; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Feeding practices: X (BF, timing of other CFB); Birth size: X (Birth weight); Gestational age: X; Other: Maternal menarcheal age, type of delivery, maternal BMI, maternal occupation, weight gain by 3mo, age of other children | [underlined: Limitations:]; Outcome assessors were not blinded; Did not use valid/reliable measures to assess outcomes (weight was self-reported; lack of detail provided); Did not account for high loss to follow-up (55%); Did not adjust for potential key confounders (sex, maternal age, race/ethnicity); Concern for multiple testing (analyzed two correlated outcomes [BMI, weight status] across many types of foods, increasing chance of false-positives; Cohort data collected over a long interval (1999-2009); Limited generalizability of CFB (i.e., animal blood is not representative of CFB in the U.S.) and due to population having very low prevalence of obesity (<2%)
Retrospective cohort studies
Burdette, 2006; Retrospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N: 372; Analytic N: 313; Attrition: ~16%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 47% Female; [underlined: Race/Ethnicity]:; 80% White; 20% Black; Parents either both black or both white; [underlined: Background Diet]:; 25% never BF; 35% EBF for 4mo; 28% BF for <6mo; 25% BF 6mo-1y; 31% BF>1y | [underlined: Intervention/Exposure:]; Age of CFB introduction: >4mo; Age: 3y; Assessment Methods:; Maternal report; [underlined: Outcomes:]; Weight status, Body Composition; Age: 5y; Assessment Methods:; Weight status: prevalance of BMI ≥85th %tile; Body composition:; - Fat-free mass, fat mass, and % body fat (DXA); - BMI, BMI %tile, BMI z-score: calculated via measured height and weight, 2000 CDC growth charts (weight/height: measured twice via digital scale and stadiometer); [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Race/ethnicity: X; Birth size: X; Other: Fat-free mass; Smoking; SNAP enrollment; maternal obesity and diabetes status, marital status | [underlined: Limitations:]; Cannot determine whether groups differed at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Non-validated measures used to assess infant feeding data; Did not adjust for potential key confounders of feeding practices and gestational age
Nested case-control/case-control studies
Bammann, 2014; Nested Case-Control Study; 8 European countries: Belgium, Cyprus, Estonia, Germany, Hungary, Italy, Spain and Sweden; [underlined: Sample Size]:; Baseline N: 1024; Analytic N: 1024; Attrition: N/A; Power Analysis and Sufficient Sample Size: Yes; OR 1.6+ can be detected at 90% power, two-sided p=0.05; [underlined: Sex:]; 50.3% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; NR | [underlined: Intervention/Exposure:]; Age of CFB introduction:<4mo; CFB: cereals, meat, vegetables or fruits; Age: 2-9y; Assessment Methods:; Caregiver report; [underlined: Outcomes:]; Weight status (Obesity); Age: 2-9y; Assessment Methods:; Weight status: risk of obesity based on IOTF categories; BMI calculated from measured weight (electronic scale) and length stadiometer; [underlined: Confounders accounted for:]; Education: X; Sex: X; Feeding practices: X; Birth size: X; Other: Country; Parent BMI; C-section; Smoking; Gestational weight gain; | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determined validity/reliability of outcome assessment; Did not adjust for key confounders (SES, race/ethnicity, maternal age; gestational age); Adjusted for maternal BMI which accounts for maternal age
Gungor, 2010; Case-Control Study; U.S.; [underlined: Sample Size]:; Baseline N: 129; Analytic N: 129 (N: 70 controls vs. N: 32 cases; N: 27 not at risk); Attrition: 0%; Power Analysis and Sufficient Sample Size: N/A; [underlined: Sex:]; 54.3% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 31% EBF ≥ 6mo; mean BF duration 4.57mo (SD: 5.37) | [underlined: Intervention/Exposure:]; Age of CFB introduction: Continuous, mo; Age: 1wk, 1, 2, 4, 6, 9, 12, 15, 18, 24mo; Assessment Methods:; Caregiver report via clincal record; [underlined: Outcomes:]; Weight status; Age: ~6.63y (SD: 0.62); Assessment Methods:; Weight, length: measured nude on digital scale to 0.01kg and stadiometer to 0.1cm by trained nurses and recorded; Weight status: overweight defined by age- and sex-specific BMI ≥ 85th percentile at ages 6, 7, 8y by CDC, 2000 standards; [underlined: Confounders accounted for:]; Education: X; Sex: X; Feeding practices: X; Birth size: X; Gestational age: X; Other: Maternal and Paternal education; Parity; Earlier weight gain at multiple intervals was included in the model from 0-6mo; 6-12mo; 12-18mo; 18-24mo; 0-24mo | [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics (i.e., other data from baseline 1 wk-24mo NR - maternal age; SES; race/ethnicity); Cannot determine reliability/validity of IV/Exposure (parental feeding data) from clinical records at ages 1wk, and 1, 2, 4, 6, 9, 12, 15, 18, 24mo; Weight status outcomes from recorded weight/height (measured via trained nurses) between 6-8y; Did not adjust for potential key confounders (maternal age; SES; race/ethnicity); Other potential confounders included in analyses as concurrent exposures showed differences between resilient vs. overweight (both parental education; EBF; earlier weight gain gain intervals differed bn groups); Small sample size (N:102 analyzed)
Hui, 2003; Case-Control Study; China; [underlined: Sample Size]:; Baseline N: 386; Analytic N: 343; Attrition: 11%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 52% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet:]; OW: 71.5% never BF; 10.8% ever BF; 17.7% BF ≥ 3mo; MW: 70.5% never BF; 18% ever BF; 11.5% BF ≥ 3mo; NW: 68.5% never BF; 19.2% ever BF; 12.3% BF ≥ 3mo | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4mo (Y/N); Age: 6-7y; Assessment Methods:; Caregiver questionnaire and interview; Diet record, 3d; [underlined: Outcomes:]; Weight status; Age: 6-7y; Assessment Methods:; Weight status: % based on derived BMI percentile: overweight group (92^nd^), normal middle-weight group (45th–55^th^), and normal low-weight group (<8^th^); [underlined: Confounders accounted for:]; Other: parental obesity | [underlined: Limitations:]; Cannot determine whether groups were similar at baseline; Cannot determine validity/reliability of outcome assessment; Did not adjust for potential key confounders (education, SES, sex, maternal age, race/ethnicity, birth size, or gestational age); Appears they treated IV separately therefore collinearity is not a concern but key confounders were not adjusted for and appeared to differ between groups
Zhou, 2011; Case-Control Study; China; [underlined: Sample Size]:; Cases: 81; Controls: 81; Attrition: N/A; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; NR | [underlined: Intervention/Exposure:]; Age of CFB introduction: <4, 4-6, >6mo; Age: 3-6y; Assessment Methods:; Parent questionnaire; [underlined: Outcomes:]; Weight status; Age: 3-6y; Assessment Methods:; Weight status: risk of obese vs. healthy weight based on age- and sex- specific BMI from IOTF categories, calculated using weight, height from kindergarten records; [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Feeding practices: X; Birth size: X (Birth weight); Gestational age: X; Other: Siblings, delivery mode, birth injuries, fetal education, pregnancy complications, small meal after kindergarten, sleep time, sports, pickiness, fast f | [underlined: Limitations:]; Cannot determine if groups were similar at baseline on key characteristics; Did not use valid/reliable measures to assess outcomes (growth measures taken from school records); Did not adjust for potential key confounders (race/ethnicity); Small sample size; Cannot rule out reverse causality