# List of abbreviations

Abbreviation: Full name
BF: Breastfed
CF: Complementary feeding
CFB: Complementary foods and beverages
FEG: Federal Expert Group
FF: Formula fed
HHS: Department of Health and Human Services
IgE: Immunoglobulin E
NEL: Nutrition Evidence Library
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
P/B-24: Pregnancy and Birth to 24 Months Project
RCT: Randomized controlled trial
TEC: Technical Expert Collaborative
USDA: United States Department of Agriculture