# WHAT IS THE RELATIONSHIP BETWEEN TIMING OF INTRODUCTION OF COMPLEMENTARY FOODS AND BEVERAGES (CFB) AND FOOD ALLERGY, ATOPIC DERMATITIS/ECZEMA, ASTHMA, AND ALLERGIC RHINITIS?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between timing of introduction of complementary foods and beverages and food allergy, atopic dermatitis/eczema, asthma, and allergic rhinitis?

### What is the answer to the question?

- Moderate evidence suggests that there is no relationship between the age at which complementary feeding first begins and risk of developing food allergy, atopic dermatitis/eczema, or asthma during childhood.
- There is insufficient evidence to determine the relationship between the age at which complementary foods or beverages are first introduced and risk of developing allergic rhinitis during childhood.

### Why was this question asked?

- This important public health question was identified and prioritized as part of the U.S. Department of Agriculture and Department of Health and Human Services Pregnancy and Birth to 24 Months Project.

### How was this question answered?

- A team of Nutrition Evidence Systematic Review staff conducted a systematic review in collaboration with a group of experts called a Technical Expert Collaborative

### What is the population of interest?

- Generally healthy infants and toddlers who were fed complementary foods and beverages from ages 0-24 months and had food allergy, atopic dermatitis/eczema, asthma, and allergic rhinitis examined through 18 years of age.

### What evidence was found?

- This review includes 31 studies.
- These studies looked at the age when a complementary food or beverage was first introduced to the infant were first introduced and food allergy, atopic dermatitis/eczema, asthma, or allergic rhinitis.
- Complementary foods and beverages are foods and beverages other than human milk or infant formula provided to an infant or young child.
- Most evidence reported no relationship between age of complementary food or beverage introduction and outcomes.
- There are limitations in the evidence as follows: use of less reliable methods to measure outcomes, only a few studies were done for some types of foods and/or outcomes, and other factors that may have had an impact on results were not always accounted for.

### How up-to-date is this review?

This review includes literature from 1/1980 to 2/2017.

## FULL REVIEW

### Systematic review question

What is the relationship between timing of introduction of complementary foods and beverages (CFB) food allergy, atopic dermatitis/eczema, asthma, and allergic rhinitis?

### Conclusion statement

Moderate evidence suggests that there is no relationship between the age at which complementary feeding first begins and risk of developing food allergy, atopic dermatitis/eczema, or asthma during childhood.

There is insufficient evidence to determine the relationship between the age at which complementary foods or beverages are first introduced and risk of developing allergic rhinitis during childhood.

### Grade

Moderate – Food allergy, atopic dermatitis/eczema, asthma; Grade Not Assignable – Allergic rhinitis

### Summary

- Thirty-one observational studies are included in this systematic review, having examined the relationship between the age of first introduction to a CFB and risk of food allergies, atopic dermatitis/eczema, asthma, and allergic rhinitis occurring during childhood through 18 years of age.
  ○ The studies included in this review examined the timing of introduction to CFB, or the age at which infants were first introduced to any foods or beverages other than human milk or infant formula were first introduced to an infant. (Note: Studies that examined the timing of introduction of specific types of CFB, including common allergenic foods, such as peanuts, eggs, and fish, are addressed in a separate review^4^).
  ○ These studies did not specify what food or beverage was first introduced. However, highly allergenic foods are not typically the first CFB introduced into an infant’s diet; therefore, it is likely that the studies in this body of evidence reflect the first introduction of cereals, fruits, and vegetables.
  ○ Nine studies examined risk of food allergy, 20 studies examined risk of eczema or atopic dermatitis, eight studies examined risk of asthma, and four studies examined risk of allergic rhinitis.
- Most evidence reported no significant associations between age of CFB introduction and risk of food allergy. While some evidence suggested that earlier first introduction of CFB may be associated with increased risk of developing food allergy, confidence in the results was restricted by methodological limitations.
- The ability to draw stronger conclusions about the relationship between the timing of first introduction to CFB and the risk of atopic disease is due to several limitations:
  ○ Use of non-validated or unreliable measures to assess risk of atopic disease (e.g., parent report of a physician diagnosis or the child’s symptoms), and assessment of outcomes later in childhood (through 10 years of age), when some atopic diseases, such as eczema, may have already resolved, or very early in childhood (3-4 months), before some atopic diseases may have occurred.
  ○ Lack of adjustment for key confounders such as consumption of human milk and/or human milk substitutes (e.g., cow’s milk formula, hydrolyzed infant formula, or fluid cow’s milk), parental smoking, and exposure to household pets
- Potential for reverse causality due to baseline atopic disease risk status impacting both the timing and types and amounts of CFB introduced, and risk of developing atopic disease.

### Description of the evidence

Thirty-one studies are included in the systematic review examining the relationship between timing of first introduction to any CFB and risk of one or more of the following: food allergy, atopic dermatitis, asthma, and allergic rhinitis occurring during childhood through 18 years (y) of age (Table 1). This table summarizes the results for each of the atopic diseases considered, and therefore, references may be repeated if they report results for two or more outcomes.

Timing of first CFB introduction was measured in a similar way across all studies, by determining the age at which a food or beverage other than human milk or infant formula was first introduced to the infant. These studies did not specify which specific CFB were introduced, but examined the age at which CF first began. However, since highly allergenic foods are not typically the first CFB introduced into an infant’s diet in the US, it is likely that the studies in this body of evidence reflect the first introduction of cereals, fruits, and vegetables. Studies did differ in terms of whether timing was analyzed as a categorical or continuous variable, what categories of ages were evaluated, and the methods used for determining age of any CFB introduction. Most studies used introduction of any CFB before 3 or 4 mo as the earliest category, and after 6 mo as the latest category, though categories ranged from introducing CFB before 8 weeks (wk) to introduction between 7 and 12 mo of age.

The included studies examined risk of food allergy, atopic dermatitis, asthma, and allergic rhinitis, which were assessed at a range of ages, from infancy through 18 y of age, using varied diagnostic methods, as described below and in Table 1.

#### Summary of findings

##### Food allergy

Nine studies included in this systematic review examined the relationship between timing of first CFB introduction and risk of developing food allergy, including 7 prospective cohort studies (1–7) and 2 nested case-control studies (8, 9) (Table 2). Data from the following cohorts were examined in multiple studies: the Prevalence of Infant Food Allergy EuroPrevall (United Kingdom) study (8, 9), and an unnamed Finnish cohort (2, 3). Most studies either exclusively enrolled or enrolled a majority of subjects who were at high risk for developing atopic disease based on family history (parent or sibling) of atopic disease (1–3, 5–7). Both studies by Kajosaari et al. (2, 3) also exclusively enrolled breast fed (BF) infants, while the other studies included subjects who were BF, formula-fed (FF), or mixed-fed.

The studies used various methods and criteria for diagnosing food allergy, though most studies applied multiple valid and reliable methods, including food challenges, which are considered to be the best method for determining food allergy, as well as skin prick tests, Immunoglobulin E (IgE) levels, occurrence of symptoms post-ingestion, and/or elimination diets, and/or food challenges. However, a few studies relied on less valid methods, such as parent report of either symptoms or physician diagnosis to determine food allergy (3, 4). Risk of food allergy was determined at various ages, ranging from 6 mo through 6 y of age. Most studies adjusted for a number of key confounders, but a few made no adjustments for potential confounders (2, 3, 7).

Five studies reported no significant associations between the timing of any CFB introduction and risk of developing food allergy (1, 3–6). Most of these studies assessed risk of food allergy at 5-6 y of age. Four remaining studies reported that earlier introduction of CFB was associated with increased risk of food allergy. Grimshaw et al. (9) reported that CFB were introduced significantly earlier in food allergy cases compared with control infants (18 vs. 20 wk), and in categorical analyses, that later CFB introduction (≥17 vs. <17 wk) was significantly associated with reduced risk of food allergy at 2 y. Grimshaw et al. (8) analyzed the same data set, distinguishing between whether the food allergy was IgE-mediated or not, and found that earlier CFB introduction was significantly associated with non-IgE-mediated food allergy at 2 y, but not IgE-mediated food allergy. Kajosaari et al. (2) reported that earlier CFB introduction (3 vs. 6 mo) was significantly associated with increased risk of food allergy at 1 y. However, their subsequent publication (3) reported that this association was no longer significant when examining risk of food allergy at 5 y. Finally, Venter et al. (7) found that earlier CFB introduction (<16 vs. >16 wk) was associated with significantly decreased risk of food allergy at 1 y and 3 y. However, this study did not account for any potential confounders.

##### Atopic dermatitis

Twenty studies included in this systematic review examined the relationship between timing of CFB introduction and atopic dermatitis, including 19 prospective cohort studies (1–3, 6, 10–24) and 1 case-control study (25) (Table 2). Data from the following cohorts were examined in multiple studies, in which outcomes were assessed in the same group of participants, but at different ages: the Lifestyle-Related Factors on the Immune System and the Development of Allergy in Childhood (Germany) study (23, 24), the German Infant Nutritional Intervention Program (12, 19), and an unnamed Finnish cohort (2, 3).

Half of the studies included a majority of subjects who were considered to be at high risk for atopic disease, having a family history (parent or sibling) of atopic disease (1–3, 6, 14, 16, 18, 20, 22–24), though most controlled for risk status in analyses (1, 6, 14, 16, 20, 23, 24). Kajosaari et al. (2, 3) also exclusively enrolled BF infants, while the other studies included subjects who were BF, FF, or mixed fed.

There was variability among studies in the methods and criteria used for diagnosing atopic dermatitis. Four studies based outcome assessment on a clinical exam done by study personnel (1, 3, 18, 19). However, most relied on less valid and/or reliable methods of parent report of symptoms or report of physician diagnosis. Age of outcome assessment occurred between 1 y and 6 y of age. Most studies adjusted for a number of key confounders, but several adjusted for only a few, or no potential confounders (2, 3, 11, 18, 22, 25).

Fifteen of the 20 studies reported no significant associations between timing of first CFB introduction and risk of developing atopic dermatitis (1, 3, 6, 10, 12, 14–19, 22–25).

The results from the studies that reported significant associations between timing of CFB introduction and risk of atopic dermatitis were mixed. Two studies found that earlier introduction of CFB was associated with increased risk of atopic dermatitis. Fergusson et al. (11) reported that earlier introduction of CFB (<4 vs. >4 mo) was significantly associated with increased risk of atopic dermatitis at 2 y. Kajosaari et al. (2) found that earlier CFB introduction (3 vs. 6 mo) was significantly associated with increased risk of atopic dematitis at 1 y. Two studies found that later introduction of CFB was significantly associated with increased risk of atopic dermatitis. Snijders et al. (20) found that later CFB introduction was significantly associated with increased risk of atopic dermatitis (3 vs 4-6 mo and 3 vs >7 mo) at 2 y. Taylor-Robinson et al. (21) found that later CFB introduction (>4 vs. <4 mo) was significantly associated with increased risk of atopic dermatitis at 5 y. Finally, Forsyth et al. (13) found that introducing CFB between 8-12 wk (vs. <8 or >12 wk) was significantly associated with greater incidence of atopic dermatitis between 53-104 wk.

In some of the studies that examined data from the same cohort, but measured outcomes at different ages, results were the same regardless of when the outcome was assessed (12, 19, 23, 24). However, 1 study reported that earlier CFB introduction was associated with increased risk of atopic dermatitis at 1 y (2), but this association was no longer significant at 5 y (3).

##### Asthma

Eight studies, including 7 prospective cohort studies and 1 case-control study, examined the relationship between timing of CFB introduction and asthma (3, 6, 16, 24, 26–29) (Table 2). Three of these studies exclusively enrolled subjects who were at high risk for developing atopic disease, with all subjects having a family history (parent or sibling) of atopic disease (3, 6, 16). Kajosaari et al. (3) also exclusively enrolled BF infants, while the other studies included subjects who were BF, FF, or mixed-fed. The studies used similar methods and criteria for diagnosing asthma, relying primarily on parent report of symptoms, with only 2 studies using a physician to diagnose asthma (6, 28). Age of outcome assessment occurred between 2 y and 15 y, with most assessing outcomes between 4 y and 7 y of age. Most studies adjusted for a number of key confounders, but Kajosaari et al. (3) did not make any adjustments for potential confounders.

Seven of the 8 studies reported no significant associations between age of CFB introduction and asthma (3, 6, 16, 24, 26, 27, 29). In a case-control study conducted in Malaysia, Nathan et al. (28) found that children with asthma (ages 3-15 y) were significantly more likely to have had earlier introduction of CFB (<6 vs. >6 mo) than control children without asthma. However, this study had a number of limitations, including lack of control for several key confounders (education, SES, race/ethnicity, birth size), and use of non-validated, unreliable measures for assessing the timing of CFB introduction, which introduced the potential for recall bias, particularly among subjects recruited at older ages.

##### Allergic rhinitis

Four prospective cohort studies included in this review examined the relationship between timing of CFB introduction and allergic rhinitis (3, 6, 22, 24) (Table 2). Three of these studies exclusively enrolled subjects who were at high risk for developing atopic disease, with all subjects having a family history (parent or sibling) of atopic disease (3, 6, 22). Kajosaari et al. (3) enrolled exclusively BF infants, while the other studies included subjects who were BF, FF, or mixed-fed. As there are no standardized criteria for diagnosing allergic rhinitis, other than the presence of typical symptoms and corresponding positive skin prick tests, these studies are difficult to evaluate, as all relied on parent report of symptoms only. Age of outcome assessment occurred at 20 mo to 2 y (6, 22) or 5-6 y of age (3, 6, 24). Neither Kajosaari et al. (3) or Van Asperen et al. (22) adjusted for any potential confounders.

Most studies reported no significant associations between age of any CFB introduction and allergic rhinitis at 20 mo (22), 2 y (6), 5 y (6), or 6 y (24). Kajosaari et al. (3) reported that earlier introduction of solids (3 vs. 6 mo) was significantly associated with increased risk of allergic rhinitis at 5 y. However, allergic rhinitis was based on parent report of symptoms, and no adjustments were made for potential confounders.

##### Atopic disease

Three studies, including 2 prospective cohort studies (3, 30) and 1 case-control study (31), examined the relationship between timing of CFB introduction and atopic disease in general (Table 2). This category included studies that found 2 or more atopic diseases in the same subject. Two of these studies exclusively enrolled subjects who were at high risk for developing atopic disease, with all subjects having a family history (parent or sibling) of atopic disease (3, 30). Kajosaari et al. (3) enrolled exclusively BF infants, while Poysa et al. (30) and Yung et al. (31) included subjects who were BF, FF, or mixed-fed. The studies varied in terms of the atopic diseases considered, diagnostic methods used, and ages when outcomes were assessed, with most relying on parent report of symptoms or a physician diagnosis. Finally, none of the studies adjusted for any potential key confounders.

All 3 studies reported no significant associations between age of CFB introduction and atopic disease, including atopic dermatitis, asthma, allergic rhinitis, and/or allergies (dust mite, food, drug, etc.) at 21 mo (31); atopic dermatitis, asthma, and/or positive skin prick test corresponding with history of food, pollen, or animal dander (birch, alm, timothy, mugwort, dog and cat epithelium, fish, milk, and wheat) at 5 y (3), or asthma, allergic rhinitis, allergic conjunctivitis, atopic dermatitis, and/or food allergy at 9 y (30).

### Evidence synthesis

Overall, moderate evidence suggests that there is no relationship between the age at which complementary feeding first begins and risk of developing food allergy, atopic dermatitis, or asthma during childhood. However, there is not enough evidence to determine whether there is a relationship with risk of developing allergic rhinitis.

Most of the evidence suggests no relationship between age of the first CFB introduction and risk of food allergy. While there is some evidence to suggest that earlier first introduction of CFB may be associated with increased risk of developing food allergy, confidence is limited by the use of the same cohort in multiple studies and concerns about the validity and reliability of methods used to assess food allergy. In addition, some studies did not account for one or more key confounders, or the specific types of CFB that were being introduced. Similarly, the preponderance of evidence suggests that there is no relationship between the age of first introduction to CFB and risk of developing atopic dermatitis and asthma. Finally, due to an inadequate number of studies with key methodological issues, it is not possible to draw conclusions about the relationship between age of CFB introduction and risk of developing allergic rhinitis.

There were several common methological limitations that could potentially lower the internal validity of the studies and reduce confidence in the findings. A number of studies used non-validated or unreliable measures (e.g., parent report of a child’s symptoms, or parent report of a physician diagnosis) to assess risk of atopic disease, particularly atopic dermatitis, asthma, and allergic rhinitis. In some cases, outcomes were assessed at inappropriate ages. For example, outcome assessment sometimes occurred later in childhood (through 10 years of age), when some atopic diseases, such as atopic dermatitis, may have already resolved, or very early in infancy (3-4 months), before atopic diseases may have emerged. In addition, there was a lack of adjustment for key confounders, such as infant milk feeding practices (e.g., human milk, cow’s milk formula, hydrolyzed infant formula, or fluid cow’s milk), parental smoking, exposure to household pets, and the types of CFB introduced.

Subjects in the studies are generalizable to the U.S. population. The studies were conducted in a number of countries that were all determined to be “very high” or “high” according to the 2014 Human Development Index (HDI, 2014). Six studies were conducted in the United Kingdom, 5 each in Finland and Germany, 4 in the US, 3 in Australia, 2 in New Zealand, and 1 study each from Hong Kong, Malaysia, Mexico, Sweden, Taiwan, and the Netherlands.

However, because many of the studies included in this review exclusively enrolled or enrolled a majority of subjects who were at higher risk than the general population for developing allergy and/or atopic disease based on family history of atopic disease, the potential for reverse causality needs to be considered. Having a family background of atopic disease, such as 1 or both parents or a sibling with a diagnosed atopic disease, is 1 of the key risk factors for development of atopic diseases. In addition, known risk status could impact the timing, types, and amounts of CFB that were introduced, as well as risk of developing various atopic diseases in early childhood. However, despite the inclusion of higher risk populations in this body of evidence, the results are probably generalizable to infants and toddlers who are lower risk for atopic disease. In addition, most studies adjusted for atopy risk status in analyses.

### Research recommendations

In order to better assess the relationship between CF and risk of atopic disease, additional research is needed that:

- Includes well-designed, targeted RCTs that address specific knowledge gaps
- Uses valid and reliable methods to assess infants’ dietary intake and established criteria, testing, and/or biomarkers to diagnose atopic disease at ages appropriate to the typical presentation of the disease
- Adjusts for key confounders, including infant milk feeding practices (e.g., human milk, cow’s milk formula, hydrolyzed infant formula, or fluid cow’s milk), parental smoking, exposure to household pets, and the types of CFB introduced
- Accounts for potential reverse causality by considering subjects’ baseline risk status for atopic disease
- Uses standard, consistent definitions of diet diversity, both in terms of the numbers and types of foods and food groups considered
- Considers the mechanisms by which specific types of foods, diet diversity, and dietary patterns may affect risk of developing atopic disease when determining which diet-health relationships to investigate, and what analyses are appropriate

### Included articles

1 Hesselmar, B, Saalman, R, Rudin, A, Adlerberth, I, Wold, A. Early fish introduction is associated with less eczema, but not sensitization, in infants. Acta Paediatr 2010;99:1861–7.20670305
2 Kajosaari, M, Saarinen, U M. Prophylaxis of atopic disease by six months’ total solid food elimination. Evaluation of 135 exclusively breast-fed infants of atopic families. Acta Paediatr Scand 1983;72:411–4.6880729
3 Kajosaari, M. Atopy prevention in childhood: the role of diet. Prospective 5-year follow-up of high-risk infants with six months exclusive breastfeeding and solid food elimination. Pediatr Allergy Immunol 1994;5:26–8.7728225
4 Luccioli, S, Zhang, Y, Verrill, L, Ramos V, M, Kwegyir A, E. Infant feeding practices and reported food allergies at 6 years of age. Pediatrics 2014.
5 McGowan, E C, Bloomberg, G R, Gergen, P J, Visness, C M, Jaffee, K F, . Influence of early-life exposures on food sensitization and food allergy in an inner-city birth cohort. J Allergy Clin Immunol 2015;135:171–8.25129677
6 Sandini U, Kukkonen AK, Poussa T, Sandini L, Savilahti E, Kuitunen M. Protective and risk factors for allergic diseases in high-risk children at the ages of two and five years. Int Arch Allergy Immunol 2011;156(3):339–48.21720181
7 Venter, C, Pereira, B, Voigt, K, Grundy, J, Clayton, C B, . Factors associated with maternal dietary intake, feeding and weaning practices, and the development of food hypersensitivity in the infant. Pediatr Allergy Immunol 2009;20:320–7.19220769
8 Grimshaw, K E, Bryant, T, Oliver, E M, Martin, J, Maskell, J, . Incidence and risk factors for food hypersensitivity in UK infants: results from a birth cohort study. Clin Transl Allergy 2015;6:1.26816616
9 Grimshaw, K E, Maskell, J, Oliver, E M, Morris, R C, Foote, K D, . Introduction of complementary foods and the relationship to food allergy. Pediatrics 2013;132.
10 Chuang, C H, Hsieh, W S, Chen, Y C, Chang, P J, Hurng, B S, . Infant feeding practices and physician diagnosed atopic dermatitis: a prospective cohort study in Taiwan. Pediatr Allergy Immunol 2011;22:43–9.20573037
11 Fergusson, D M, Horwood, L J, Beautrais, A L, Shannon, F T, Taylor, B. Eczema and infant diet. Clin Allergy 1981;11:325–31.7296805
12 Filipiak, B, Zutavern, A, Koletzko, S, von B, A, Brockow, I, . Solid food introduction in relation to eczema: results from a four-year prospective birth cohort study. J Pediatr 2007;151:352–8.17889067
13 Forsyth, J S, Ogston, S A, Clark, A, Florey, C D, Howie, P W. Relation between early introduction of solid food to infants and their weight and illnesses during the first two years of life. Bmj 1993;306(6892):1572–6.8329916
14 Illi S, von Mutius E, Lau S, Nickel R, Gruber C, Niggemann B, Wahn U. The natural course of atopic dermatitis from birth to age 7 years and the association with asthma. J Allergy Clin Immunol 2004;113(5):925–31.15131576
15 Joseph, C L, Ownby, D R, Havstad, S L, Woodcroft, K J, Wegienka, G, . Early complementary feeding and risk of food sensitization in a birth cohort. J Allergy Clin Immunol 2011;127.
16 Mihrshahi, S, Ampon, R, Webb, K, Almqvist, C, Kemp, A S, . The association between infant feeding practices and subsequent atopy among children with a family history of asthma. Clin Exp Allergy 2007;37:671–9.17456214
17 O’Donovan, S M, O’B H, Murray, D M, Kenny, L C, Khashan, A S, Chaoimh, . Neonatal adiposity increases the risk of atopic dermatitis during the first year of life. J Allergy Clin Immunol 2016;137:108–17.26194543
18 Poysa, L, Remes, K, Korppi, M, Juntunen B, K. Atopy in children with and without a family history of atopy. I. Clinical manifestations, with special reference to diet in infancy. Acta Paediatr Scand 1989;78:896–901.2603716
19 Schoetzau, A, Filipiak P, B, Franke, K, Koletzko, S, Von B, A, . Effect of exclusive breast-feeding and early solid food avoidance on the incidence of atopic dermatitis in high-risk infants at 1 year of age. Pediatr Allergy Immunol 2002;13:234–42.12390439
20 Snijders, B E, Thijs, C, van R, R, van den B, P A. Age at first introduction of cow milk products and other food products in relation to infant atopic manifestations in the first 2 years of life: the KOALA Birth Cohort Study. Pediatrics 2008;122.
21 Taylor R, D C, Williams, H, Pearce, A, Law, C, Hope, S. Do early-life exposures explain why more advantaged children get eczema? Findings from the U.K. Millennium Cohort Study. Br J Dermatol 2016;174:569–78.26595368
22 Van A, P P, Kemp, A S, Mellis, C M. Relationship of diet in the development of atopy in infancy. Clin Allergy 1984;14:525–32.6509767
23 Zutavern, A, Brockow, I, Schaaf, B, Bolte, G, von B, A, . Timing of solid food introduction in relation to atopic dermatitis and atopic sensitization: results from a prospective birth cohort study. Pediatrics 2006;117:401–11.16452359
24 Zutavern, A, Brockow, I, Schaaf, B, von B, A, Diez, U, . Timing of solid food introduction in relation to eczema, asthma, allergic rhinitis, and food and inhalant sensitization at the age of 6 years: results from the prospective birth cohort study LISA. Pediatrics 2008;121.
25 Estrada R, E, Pardo C, M G, Toledo B, M E, Lerma O, M L, del R-N, B, . A case-control study of food hyper-sensitivity, timing of weaning and family history of allergies in young children with atopic dermatitis. Allergol Immunopathol (Madr) 2007;35:101–4.17594873
26 Fergusson, D M, Horwood, L J, Shannon, F T. Asthma and infant diet. Arch Dis Child 1983;58:48–51.6830275
27 Hetzner, N M, Razza, R A, Malone, L M, Brooks G, J. Associations among feeding behaviors during infancy and child illness at two years. Matern Child Health J 2009;13:795–805.18839293
28 Nathan, A M, de B, J, Khalid, F, Arumugam, K. Caesarean section and asthma in Malaysian children: a case-control study. Asian Pac J Allergy Immunol 2012;30:204–8.23156850
29 Wilson, A C, Forsyth, J S, Greene, S A, Irvine, L, Hau, C, . Relation of infant diet to childhood health: seven year follow up of cohort of children in Dundee infant feeding study. Bmj 1998;316(7124):21–5.9451261
30 Poysa, L, Korppi, M, Remes, K, Juntunen B, K. Atopy in childhood and diet in infancy. A nine-year follow-up study. I. Clinical manifestations. Allergy Proc 1991;12:107–11.2060780
31 Yung, J, Yuen, J W, Ou, Y, Loke, A Y. Factors associated with atopy in toddlers: a case-control study. Int J Environ Res Public Health 2015;12:2501–20.25723646
32 United Nations Development Programme. Human Development Report 2014. Sustaining Human Progress: Reducing Vulnerabilities and Building Resilience. New York, 2014.
33 The World Bank. Internet: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-bank-country-and-lending-groups (accessed March 27, 2018).

Table 1 Description of studies examining the relationship between the timing of introduction of complementary foods and beverages (CFB) and food allergy, atopic dermatitis/eczema, asthma, and allergic rhinitis

References; Subject Characteristics (Sample Size, Sex, Race/Ethnicity, Atopic Disease Risk Status; Background Diet) | Independent Variable/Exposure, Outcomes | Confounders, Limitations
Chuang, 2011; Prospective Cohort Study; Taiwan (Taiwan Birth Cohort Study); Sample Size:; Baseline N: 24200; Analytic N: 18733; Attrition: 23%; Sample Size Calculation: NR; Sex: 48% Female; Race/Ethnicity: NR; Atopic Disease Risk Status: 30% had parental allergic history; excluded children with doctor-diagnosed atopic dermatitis from 0-6mo; Background Diet: 26.9% BF within 1mo | Intervention/Exposure:; Age of CFB introduction: <4, 4-6, >6mo; Assessment Methods: Maternal interview; Outcomes:; Atopic dermatitis; Age: 18mo; Assessment Methods:; Atopic dermatitis: Maternal report of physician diagnosis | Confounders:; The following confounders were accounted for: Education; Sex; Feeding practices; Birth size; Gestational age; Smoking; Atopy risk status; Pets in home; Mold in home; Birth order; Parent age; Residence; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Did not account for high attrition; Outcome assessors were not blinded; Did not use valid/reliable methods for assessing outcomes (parent report); Did not adjust for key confounders (SES, race/ethnicity); Limited generalizability due to enrollment of population at high risk for atopic disease
Estrada-Reyes, 2007; Case-Control Study; Mexico; Sample Size:; Cases: 28; Controls: 28; Attrition: 0%; Sample Size Calculation: NR; Sex: 50% Female; Race/Ethnicity: NR; Atopic Disease Risk Status: 45% had family allergic history; Background Diet: NR | Intervention/Exposure:; Age of CFB introduction: <6, >6mo; Assessment Methods: Maternal interview; Outcomes:; Atopic dermatitis; Age: <3y; Assessment Methods:; Atopic dermatitis: Maternal report, confirmed by study personnel | Confounders:; The following confounders were accounted for: Atopy risk status; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Outcome assessors were not blinded; Did not adjust for key confounders (education, SES, sex, race/ethnicity, feeding practices, birth size, gestational age, smoking); Small sample size; study may have been underpowered
Fergusson, 1981; Prospective Cohort Study; New Zealand (Christchurch Health and Development Study); Sample Size:; Baseline N: 1262; Analytic N: 1156; Attrition: 8%; Sample Size Calculation: NR; Sex: NR; Race/Ethnicity: NR; Atopic Disease Risk Status: 24% had parental atopy history; Background Diet: EBF at 4mo: 19% | Intervention/Exposure:; Age of CFB introduction: <4, >4mo; Assessment Methods: Maternal interview, food diary; Outcomes:; Eczema; Age: 2y; Assessment Methods:; Eczema: Maternal report; with some physician validation | Confounders:; The following confounders were accounted for: Feeding practices; Atopy risk status; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine recruitment methods, baseline characteristics, confounding factors, or blinding methods; Outcome assessors were not blinded; Did not adjust for key confounders (education, SES, sex, race/ethnicity, feeding practices, birth size, gestational age, smoking); Limited generalizability due to lower rates of exclusive BF that may not be representative of current infant feeding practices
Fergusson, 1983; Prospective Cohort Study; New Zealand (Christchurch Health and Development Study); Sample Size:; Baseline N: 1265; Analytic N: 1110; Attrition: 12%; Sample Size Calculation: NR; Sex: NR; Race/Ethnicity: NR; Atopic Disease Risk Status: 11% had parental asthma history; Background Diet: EBF at 4mo: 19% | Intervention/Exposure:; Age of CFB introduction: <4, >4mo; Assessment Methods: Maternal interview, food diary; Outcomes:; Asthma; Age: 4y; Assessment Methods:; Asthma: Maternal report of physician diagnosis, or history of wheezy bronchitis, with some physician validation | Confounders:; The following confounders were accounted for: Feeding practices; Atopy risk status; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine recruitment methods, baseline characteristics, confounding factors, or blinding methods; Outcome assessors were not blinded; Did not use valid/reliable measures to assess outcomes; Did not adjust for key confounders (education, SES, sex, race/ethnicity, birth size, gestational age, smoking); Limited generalizability due to lower rates of exclusive BF that may not be representative of current infant feeding practices
Filipiak, 2007; Prospective Cohort Study; Germany (German Infant Nutritional Intervention Program); Sample Size:; Baseline N: 5991 (N: 2252 in intervention group, N: 3739 in non-intervention group); Analytic N: 4753; Attrition: 21%; Sample Size Calculation: NR; Sex: NR; Race/Ethnicity: NR; Atopic Disease Risk Status: ~22% had familial history of eczema (40% in intervention group, 10% in non-intervention group); 100% of subjects in the intervention group had family history of atopic disease; Background Diet: EBF at 4mo: 50% | Intervention/Exposure:; Age of CFB introduction: 1-4, 5-6, 7-12mo; Assessment Methods: Parent questionnaire; Outcomes:; Eczema; Age: 4y; Assessment Methods:; Eczema: Parent report of doctor diagnosis or recurrent symptoms lasting for 6mo up to 1y and 2wk at 2-4y | Confounders:; The following confounders were accounted for: Education; Sex; Feeding practices; Birth size; Gestational age; Smoking; Atopy risk status; Study region; siblings; pets); Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Outcome assessors (parent report) were not blinded; Outcomes were not assessed using valid measures (parent report of physician diagnosis); Difficult to determine attrition rates based on sample sizes presented in text/tables; Did not adjust for key confounders (SES, race/ethnicity, gestational age); Multi-component intervention may have confounded outcome (randomization to different formulas+ recommendations); Sample size calculations not reported.
Forsyth, 1993; Prospective Cohort Study; Scotland; Sample Size:; Baseline N: 671; Analytic N: 544 at 26wk, 548 at 52wk, 392 at 104wk; Attrition: 19% at 26wk and 52wk, 50% at 104wk; Sample Size Calculation: NR; Sex: 52% Female; Race/Ethnicity: NR; Atopic Disease Risk Status: NR; Background Diet: BF at 13wk: 14% EBF, 19.3% PBF, 66% MF | Intervention/Exposure:; Age of CFB introduction: <8, 8-12, >12wk; Assessment Methods: Maternal questionnaire; Outcomes:; Eczema; Age: Asthma: 14-26wk; Eczema: 53wk-104wk (~1-2y); Assessment Methods:; Eczema: Parent report, medical record review; presence of itchy rash | Confounders:; The following confounders were accounted for: SES; Sex; Feeding practices; Birth size; Smoking; Atopy risk status; Maternal age; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine validity/reliability of measures used to assess outcomes; High-attrition (50%) at 104wk not accounted for in analyses; Did not adjust for key confounders (education, race/ethnicity, gestational age)
Grimshaw, 2013; Nested Case-Control Study; United Kingdom (Prevalence of Infant Food Allergy EuroPrevall); Sample Size:; Cases: 41; Controls: 82; Attrition: 0%; Sample Size Calculation: NR; Sex: 46% Female; Race/Ethnicity: 95% Caucasian; Atopic Disease Risk Status: 27% cases vs. 13% controls had maternal asthma; 54% vs. 38% had maternal allergy; Background Diet: 94% initiated BF, 50% EBF at 9 weeks; Median BF duration 22wk, Median EBF duration 7 wk; CFB introduced at 20.3wk | Intervention/Exposure:; Age of CFB introduction: Age in weeks, continuous; Assessment Methods: Food diary; Outcomes:; Food allergy; Age: 2y; Assessment Methods:; Food allergy: Parent report with clinical history, IgE≥0.35 and/or SPT wheal ≥3mm; exclusion diet with improved symptoms; and DBPCFC (including delayed reactions up to 48hr after the challenge) | Confounders:; The following confounders were accounted for: Education; Sex; Feeding practices; Smoking; Atopy risk status; Pet ownership; Maternal Age; Single birth; Limitations:; Cannot determine whether participants were similar at baseline on key characteristics; Did not adjust for key confounders (SES, race/ethnicity, birth size, gestational age); Small sample size; study may have been underpowered
Grimshaw, 2016; Nested Case-Control Study; United Kingdom (Prevalence of Infant Food Allergy EuroPrevall); Sample Size:; Cases: 41; Controls: 82; Attrition: 0%; Sample Size Calculation: NR; Sex: 49 % Female; Race/Ethnicity: 95% Caucasian; Atopic Disease Risk Status: 67% had maternal atopy; 54% had paternal atopy; 22% had maternal food allergy; 12% had paternal food allergy; Background Diet: 94% initiated BF, 50% EBF at 9 weeks; Median BF duration 22wk, Median EBF duration 7 wk; CFB introduced at 20.3wk | Intervention/Exposure:; Age of CFB introduction: Age in weeks, continuous; Assessment Methods: Food diary; Outcomes:; Food allergy (IgE and non-IgE mediated); Age: 2y; Assessment Methods:; Food allergy: Parent report with clinical history, IgE≥0.35 and/or SPT wheal ≥3mm; exclusion diet with improved symptoms; and DBPCFC (including delayed reactions up to 48hr after the challenge) | Confounders:; The following confounders were accounted for: Gestational age; Atopy risk status; Child age; Dog at home; Received skin creams, powders, lotions; No nut/peanut intake during pregnancy; Reduced soy intake during BF; Limitations:; Cannot determine whether participants were similar at baseline on key characteristics; Did not adjust for key confounders (SES, pets); Small sample size; study may have been underpowered
Hesselmar, 2010; Prospective Cohort Study; Sweden (ALLERGY-FLORA); Sample Size:; Baseline N: 207; Analytic N: 184; Attrition: 11%; Sample Size Calculation: NR; Sex: 50% Female; Race/Ethnicity: NR; Atopic Disease Risk Status: 80% had both parents, 49% maternal, 41% paternal history of asthma, AR, or eczema; Background Diet: 88% BF; 76% still PBF at 6mo; Formula introduced ~5mo; median duration EBF 4mo, PB 7.5mo; Age introduced to solids (potatoes, root/vegetables, meats) 4mo; fruit 5mo; fish 10mo; hen’s egg 12mo | Intervention/Exposure:; Age of CFB introduction: Age in months, continuous (CFB: potatoes, root vegetables, vegetables, and meat); Assessment Methods: Food diary; Outcomes:; Food allergy, eczema, asthma; Age: 18mo; Assessment Methods:; Food allergy: Symptoms (immediate or late-onset reaction) after food ingestion, with OFC, and/or food-specific IgE, SPT wheal ≥3mm, and/or GI biopsy/multi-organ reactions; Eczema: Clinical exam | Confounders:; The following confounders were accounted for: Sex; Feeding practices; Gestational age; Atopy risk status; Limitations:; Cannot determine whether participants were similar at baseline on key characteristics of race/ethnicity, SES, education, birth size/weight, or smoking exposure; Cannot determine whether outcome assessors were blinded; Did not adjust for key confounders (education, SES, race/ethnicity, birth size, smoking); CFB included only “non allergenic” foods; allergenic foods examined seperately
Hetzner, 2009; Prospective Cohort Study; United States (Early Child Longitudinal Study-Birth Cohort); Sample Size:; Baseline N: 10700; Analytic N: 7900; Attrition: 26%; Sample Size Calculation: NR; Sex: 49% Female; Race/Ethnicity: 54% White-Non Hispanic; 13% Black-African American-Non Hispanic; 26% Hispanic; 3% Asian; Atopic Disease Risk Status: NR; Background Diet: 70% initiated BF; 78% introduced formula<6mo; 74% introduced to CFB<6mo; 15% introduced finger-foods <6mo | Intervention/Exposure:; Age of CFB introduction: <6, >6mo; Assessment Methods: Maternal interview; Outcomes:; Asthma; Age: 2y; Assessment Methods:; Asthma: Maternal report | Confounders:; The following confounders were accounted for: Education; SES; Sex; Race/ethnicity; Feeding practices; Birth size; Smoking; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Outcome assessors were not blinded; Outcome measures used were not valid/reliable (maternal report of asthma with no criteria or definition provided, and at an arly age when asthma diagnoses are less reliable); Did not adjust for key confounders (gestational age, atopy risk status)
Illi, 2004; Prospective Cohort Study; German (German Multicenter Atopy Study); Sample Size:; Baseline N: 1314; Analytic N: 858; Attrition: 35%; Sample Size Calculation: NR; Sex: NR; Race/Ethnicity: NR; Atopic Disease Risk Status: 73% had parental atopy history; Background Diet:; 92% initiated BF; 49% received supplements in first days of life (36% of which was cow’s milk formula, often partially hydrolyzed); 53% introduced CFB <3mo; atopic parents introduced CFB later than non-atopic parents | Intervention/Exposure:; Age of CFB introduction: Quartiles (not described); Assessment Methods: Parent interview; Outcomes:; Atopic dermatitis; Age: 2y; Assessment Methods:; Atopic dermatitis: Parent report of physician diagnosis or symptoms; or visible atopic dermatitis at follow-up | Confounders:; The following confounders were accounted for: Education; Sex; Feeding practices; Smoking; Atopy risk status; Pets; older siblings; # of infectious diseases; Limitations:; Cannot determine whether participants were similar at baseline on key characteristics of SES, race/ethnicity, birth size, or gestational age; Outcome assessors were not blinded; Outcome measures used were not valid/reliable; Did not adjust for key confounders (SES, race/ethnicity, birth size, gestational age); Did not describe categories (quartiles) anlyzed for age of CFB introduction; did not show data for analyses wih risk of AD, and did not report whether analyses were done for other outcomes reported in the study (food allergen sensitization, asthma, wheeze)
Joseph, 2011; Prospective Cohort Study; United States (Wayne County Health, Environment, Allergy and Asthma Longitudinal (WHEALS) Study); Sample Size:; Baseline N: 1258; Analytic N: 594; Attrition: 53%; Sample Size Calculation: NR; Sex: NR; Race/Ethnicity: 61% Black; Atopic Disease Risk Status: 45% had parental history of atopy; Background Diet: 77% ever BF; 73% BF <6mo; 40% introduced to CFB <4mo | Intervention/Exposure:; Age of CFB introduction: <4, >4mo; Assessment Methods: Parent interview; Outcomes:; Atopic dermatitis; Age: 2-3y; Assessment Methods:; Atopic dermatitis: NR | Confounders:; The following confounders were accounted for: Education; SES; Sex; Race/ethnicity; Feeding practices; Smoking; Atopy risk status; Birth order; Marital status; Limitations:; Cannot determine whether participants were similar at baseline on key characteristics of gestational age or birth weight; Cannot determine whether outcome assessors were blinded; Validity/Reliability of measures used not clear; Did not adjust for key confounders (birth size, gestational age); Asthma defined as early childhood wheezing
Kajosaari, 1983; Prospective Cohort Study; Finland; Sample Size:; Baseline N: 135; Analytic N: 135; Attrition: N/A; Sample Size Calculation: NR; Sex: NR; Race/Ethnicity: NR; Atopic Disease Risk Status: 100% had familial risk (either parent either asthma or allergy); Background Diet: EBF to 6mo: 52%; no infants received formula; Age of CFB introduction: 48% by 3mo | Intervention/Exposure:; Age of CFB introduction: ~3, 6mo; Assessment Methods: NR; Outcomes:; Food allergy, eczema; Age: 1y; Assessment Methods:; Food allergy: History of skin rash or vomiting after ingestion, confirmed by elimination diet and home challenges; Eczema: Parent report of physician diagnosis of eczema, and/or diagnosis by study personnel | Confounders:; No confounders were adjusted for; Limitations:; Outcome assessors were not blinded; Cannot determine whether participants were similar on any baseline characteristics; Did not adjust for key confounders (education, SES, sex, race/ethnicity, feeding practices, birth size, gestational age, smoking, atopy risk status); Did not use valid/reliable measures for outcome measure for food allergy; Limited generalizability due to exclusive enrollment of high risk infants
Kajosaari, 1994; Prospective Cohort Study; Finland; Sample Size:; Baseline N: 135; Analytic N: 135; Attrition: N/A; Sample Size Calculation: NR; Sex: NR; Race/Ethnicity: NR; Atopic Disease Risk Status: 100% had familial risk (either parent either asthma or allergy); Background Diet: EBF to 6mo: 52%; no infants received formula; Age of CFB introduction: 48% by 3mo | Intervention/Exposure:; Age of CFB introduction: ~3, 6mo; Assessment Methods: NR; Outcomes:; Food allergy, atopic eczema, asthma, allergic rhinitis, atopic disease; Age: 5y; Assessment Methods:; Food allergy: Parent report of repeated skin rash, urticaria or heavy vomiting after ingestion; Atopic eczema: Examination by study personnel; Asthma: Parent reported asthma diagnosis; Allergic rhinitis: History of seasonal symptoms (nasal discharge, itching conjunctivities, wheezing) during pollen season or associated with animal contacts; Atopic disease: Atopic eczema, asthma, or positive SPT corresponding with history of food, pollen, or animal dander (birth, alm, timothy, mugwort dog & cat epithelium, fish, milk, & wheat | Confounders:; No confounders were adjusted for; Limitations:; Outcome assessors were not blinded; Cannot determine whether participants were similar on any baseline characteristics; Did not adjust for key confounders (education, SES, sex, race/ethnicity, feeding practices, birth size, gestational age, smoking, atopy risk status); Did not use valid/reliable measures to assess outcomes, especially food allergy Limited generalizability due to exclusive enrollment of high risk infants; Small sample size; study may have been underpowered
Luccioli, 2014; Prospective Cohort Study; United States (Infant Feeding Practices Study II Year 6 Follow-Up Study); Sample Size:; Baseline N: 1531; Analytic N: 1363; Attrition: 12%; Sample Size Calculation: NR; Sex: 51% Female; Race/Ethnicity: 86% White Non-Hispanic; 2% Asian Non-Hispanic; 4% Black Non-Hispanic; 6% Hispanic; 2% Other; Atopic Disease Risk Status: 23% had parent history of food allergy; 44% had parent history of atopy; Background Diet: 43% EBF at 0mo, 30% at 1-3mo, 27% at 4mo+; Introduced to CFB: 34% at 1-3mo; 40% at 4-5mo; 17% at 6-12mo; 9% NR | Intervention/Exposure:; Age of CFB introduction: 1-3/<4, 4-5, 6-12mo, NR; Assessment Methods: Maternal questionnaire; Outcomes:; Food allergy; Age: 6y; Assessment Methods:; Food allergy: Maternal report of physician diagnosis | Confounders:; The following confounders were accounted for: Education; SES; Sex; Race/ethnicity; Feeding practices; Smoking; Atopy risk status; Delivery mode; Parity; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Outcome assessors were not blinded; Outcome measures used were not valid/reliable; Did not adjust for key confounders (birth size, gestational age)
McGowan, 2015; Prospective Cohort Study; United States (Urban Environment and Childhood Asthma) (URECA); Sample Size:; Baseline N: 609; Analytic N: 516; Attrition: 15%; Sample Size Calculation: NR; Sex: 56% Female; Race/Ethnicity: 61% Black, 16% Hispanic, 7% Other; Atopic Disease Risk Status: 80% had parental history of allergic rhinitis, eczema, or asthma; Background Diet: 44% ever BF, 18% BF at 3mo; CFB introduced at 15wk (SD=~8.5wk) | Intervention/Exposure:; Age of CFB introduction: Age in wk, continuous; Assessment Methods: Maternal interview; Outcomes:; Food allergy; Age: 5y; Assessment Methods:; Food allergy: Positive IgE level (>0.35 kU/L) to milk, egg, and/or peanut, avoidance of sensitized foods, and clinical confirmation (parent report of previous food reaction to milk, egg or peanut; or classified as FA by allergist consult) | Confounders:; The following confounders were accounted for: Sex; Gestational age; Atopy risk status; Site; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Limited information provided about CFB assessment; Did not use valid/reliable measures to diagnose food allergy; Cannot determine whether outcome assessors were blinded; Did not adjust for key confounders (education, SES, race/ ethnicity, feeding practices, birth size, smoking); Generalizability limited to inner-city children in small number of US cities with parental history of allergy/asthma; Large number of subjects classified as “possibly allergic” and weren’t included in analyses
Mihrshahi, 2007; Prospective Cohort Study; Australia; (Childhood Asthma Prevention Study); Sample Size:; Baseline N: 616; Analytic N: 516; Attrition: 16%; Sample Size Calculation: NR; Sex: NR; Race/Ethnicity: NR; Atopic Disease Risk Status: 100% had one or more parents or siblings had asthma or wheezing; Background Diet: 90% ever BF, 34% EBF at 3mo, 2% EBF at 6mo; CFB introduced by 26% at 3mo | Intervention/Exposure:; Age of CFB introduction: <3, >3mo; Assessment Methods: Maternal interview; Outcomes:; Eczema, asthma; Age: 5y; Assessment Methods:; Eczema: Presence of flexural eczema, or a history of itchy rash coming and going for >3mo, and at least one of the following: seeking medical care for diagnosed eczema/atopic dermatitis or using steroid or emollient creams in the last 12mo; Asthma (probable current): Any wheeze in last 12mo in children who either had asthma diagnosed by a doctor or at a hospital, or a positive bronchodilator test | Confounders:; The following confounders were accounted for: Education; Sex; Feeding practices; Birth size; Gestational age; Smoking; Atopy risk status; Intervention group; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Did not use valid/reliable measures to assess all outcomes (asthma); Did not adjust for key confounders (SES, race/ethnicity); Generalizability limited to those with a family history of asthma
Nathan, 2012; Case-Control Study; Malaysia; Sample Size:; Asthma Cases: 78; Controls: 78; Attrition: NA; Sample Size Calculation: NR; Sex: 46% Female; Race/Ethnicity: 65% Malay, 13% Chinese, 22% Indian; Atopic Disease Risk Status: 77% cases vs 21% controls had family history of atopy, 80% vs 21% had family history of asthma; Background Diet: 28% were EBF >6mo | Intervention/Exposure:; Age of CFB introduction: <6, >6mo; Assessment Methods: Parent questionnaire; Outcomes:; Asthma; Age: 3-15y; Assessment Methods:; Asthma: Recurrent episodes of doctor-diagnosed wheezing with use of acute reliever and/or inhaler medication | Confounders:; The following confounders were accounted for: Sex; Feeding practices; Gestational age; Smoking; Atopy risk status; Mode of delivery; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Did not use valid/reliable measures, particularly for assessing timing of CFB introduction; Cannot determine whether length of follow-up was similar between groups; Did not adjust for key confounders (Education, SES, race/ethnicity, birth size); Potential for recall bias, particularly among subjects recruited at older ages; Study may have been underpowered
O’Donovan, 2016; Prospective Cohort Study; United Kingdom (Cork BASELINE Study); Sample Size:; Baseline N: 1,537; Analytic N: 709; Attrition: 54%; Sample Size Calculation: NR; Sex: 48% Female; Race/Ethnicity: NR; Atopic Disease Risk Status: 43% had maternal family history or atopy, 34% had parental family history of atopy; Background Diet: 14% EBF at 2mo; 22% BF at 6mo; 19% introduced to CFB by 17wk, 6% introduced >26wk | Intervention/Exposure:; Age of CFB introduction: <17, >26wk; Assessment Methods: Maternal interview; Outcomes:; Atopic dermatitis; Age: 12mo; Assessment Methods:; Atopic dermatitis: Parent report, with formal diagnosis using UK Working Party Diagnostic Criteria | Confounders:; The following confounders were accounted for: Education; Sex; Feeding practices; Birth size; Smoking; Atopy risk status; Domestic pet, body composition, cord vitamin D status, season of birth, rural/urban, maternal alcohol and vit D intake at 15wk, C-section, marital status, maternal BMI, maternal age; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Outcome assessors were not blinded; Did not adjust for key confounders (SES, race/ethnicity, gestational age); Did not assess the impact of high loss to follow-up (>50% by 12mo)
Poysa, 1989; Prospective Cohort Study; Finland; Sample Size:; Baseline N: 100; Analytic N: 70; Attrition: 30%; Sample Size Calculation: NR; Sex: NR; Race/Ethnicity: NR; Atopic Disease Risk Status: All subjects had family atopy history; Background Diet: Subjects with atopy history advised to BF for >3mo, to not introduce formula or cow’s milk before 3mo, and to avoid the “classic dietary allergens until 9mo; 52% followed this diet; BF: 24% <3mo, 14% 3-6mo, 61% >6mo; FF: 36% <3mo, 30% 3-6mo, 44% >6mo; CFB: 23% <3mo, 73% 3-6mo, 4% >6mo | Intervention/Exposure:; Age of CFB introduction: <3, 3-6, >6mo (CFB: avoided “classic dietary allergens” until 9mo); Assessment Methods: Parent questionnaire; Outcomes:; Atopic dermatitis; Age: 5y; Assessment Methods:; Atopic dermatitis: Diagnosis by a dermatologist; pruritic dermatitis accompanied by dry skin on the face in infancy and on flexural surfaces of the extremities later | Confounders:; No confounders were adjusted for; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Did not adjust for key confounders (SES, sex, education, race/ethnicity, birth size, gestational age, feeding practices, atopy risk status, smoking); Did not account for high loss to follow-up (~30%); Did not report statistical results of analyses; Limited generalizability due to exclusive enrollment of high risk infants
Poysa, 1991; Prospective Cohort Study; Finland; Sample Size:; Baseline N: 100; Analytic N: 68; Attrition: 32%; Sample Size Calculation: NR; Sex: NR; Race/Ethnicity: NR; Atopic Disease Risk Status: 100% had family history of atopy; Background Diet: Subjects with atopy history advised to BF for >3mo, to not introduce formula or cow’s milk before 3mo, and to avoid the “classic dietary allergens until 9mo; 52% followed this diet; BF: 24% <3mo, 14% 3-6mo, 61% >6mo; FF: 36% <3mo, 30% 3-6mo, 44% >6mo; CFB: 23% <3mo, 73% 3-6mo, 4% >6mo | Intervention/Exposure:; Age of CFB introduction: <3, 3-6, >6mo; Assessment Methods: Parental questionnaire; Outcomes:; Atopy; Age: 9y; Assessment Methods:; Atopy: Parent report of physician diagnosis of asthma, allergic rhinitis, allergic conjunctivitis, atopic dermatitis (diagnosis made by dermatologist), and/or food allergy; allergies to fruit and or apple tested at home (elimination diet) and allergies to eggs or fish confirmed by hospital challenge) | Confounders:; No confounders were adjusted for; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Did not account for high loss to follow-up (~30%); Did not use valid/reliable measures to measure outcomes; Did not adjust for key confounders (SES, sex, education, race/ethnicity, birth size, gestational age, feeding practices, atopy risk status, smoking)
Sandini, 2011; Prospective Cohort Study; Finland; Sample Size:; Baseline N: 1223; Analytic N: 925 at 2y, 891 at 5y; Attrition: 24% at 2y, 27% at 5y; Sample Size Calculation: Yes, but based on RCT of probiotics for allergy prevention conducted in this same population; Sex: 50% Female; Race/Ethnicity: NR; Atopic Disease Risk Status: 100% had at least one parent with an allergic disease; Background Diet: 45% EBF for 2-4mo, 61% BF >6mo, solids started at ~4mo (SD=0.7), with 67% ≥4mo | Intervention/Exposure:; Age of CFB introduction: <4, >4mo; Assessment Methods: Parent questionnaire; Outcomes:; Food allergy, eczema, asthma, allergic rhinitis; Age: 2y, 5y; Assessment Methods:; Food allergy: OFC in infants whose food-related symptoms (urticaria, eczema, vomiting, loose stools, abdominal pain, and excessive crying) improved during a 2wk elimination diet; Eczema: Itchy skin plus all or 3 of the following: history of atopic disease in the family, dry skin during the last year, history of eczema, or visible eczema involving typical sites; Asthma: 2+ physician-diagnosed wheezing episodes with persistent cough or as exercise-induced (including giggling and crying) symptoms; verified by the study pediatrician review of patient records; Allergic rhinitis: Allergen-specific sensitization with a history of 2 or more symptoms (nasal discharge, blockage, or sneezing/itching) recurrently during antigen contact | Confounders:; The following confounders were accounted for: Sex; Feeding practices; Gestational age; Smoking; Atopy risk status; Delivery mode, siblings, antibiotic use, airway infections, dog/cat exposure; RCT study group; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Did not adjust for key confounders (SES, race/ethnicity, birth size); Outcome assessors were not blinded; Did not define age of CFB introduction; Limited generalizability due to exclusive enrollment of high risk infants
Schoetzau, 2002; Prospective Cohort Study; Germany(German Infant Nutritional Intervention Program); Sample Size:; Baseline N: 2252; Analytic N: 1121; Attrition: 50%; Sample Size Calculation: NR; Sex: 49% Female; Race/Ethnicity: NR; Atopic Disease Risk Status: 42% had 1+ core family members with atopic dermatitis; all infants had extended family members with some atopic disease; Background Diet: 23% formula fed, 77% BF | Intervention/Exposure:; Age of CFB introduction: 1-16, 17-24, >24wk; Assessment Methods: Food diary; Outcomes:; Atopic dermatitis; Age: 1y; Assessment Methods:; Atopic dermatitis: Physician diagnosis defined by a combination of diagnostic criteria, including typical morphology and distribution of skin lesions (face, neck and scalp, flexural folds, hands and extensor sides of extremities); pruritus (signs of scratching); and a tendency towards chronicity (duration of least 14d and/or relapsing) | Confounders:; The following confounders were accounted for: Education; Sex; Race/ethnicity; Feeding practices; Gestational age; Smoking; Atopy risk status; Pets; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Did not account for high loss to follow-up (>50% by 1y); Did not adjust for key confounders (SES, birth size)
Snijders, 2008; Prospective Cohort Study; The Netherlands (KOALA Birth Cohort Study); Sample Size:; Baseline N: 2834; Analytic N: 2558; Attrition: 10%; Sample Size Calculation: NR; Sex: 49% Female; Race/Ethnicity: NR; Atopic Disease Risk Status: 60% had parental allergic disease, 19% had sibling allergic disease; Background Diet: 15% never BF, 33% BF 0-3mo, 17% BF 4-6mo, 15% BF 7-9mo, 17% BF >9mo; 39% introduced to cow milk products by 3mo; 89% introduced to other solid foods from 4-6mo | Intervention/Exposure:; Age of CFB introduction: <3, 4-6, >7mo; Assessment Methods: Parent questionnaire; Outcomes:; Eczema/atopic dermatitis; Age: 2y; Assessment Methods:; Eczema: Parent report of itchy rash; Atopic dermatitis: Parent report of the presence of itchy rash, history of flexural dermatitis,, presence of visible flexural dermatitis, and onset before 2y; UK AD scoring system with home visit and visualization of skin at 2y) | Confounders:; The following confounders were accounted for: Education; Sex; Feeding practices; Smoking; Atopy risk status; Conventional/ alternative lifestyle; Maternal age at delivery; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Outcome assessors were not blinded; Did not use valid/reliable measures (parent reported outcomes); Did not adjust for key confounders (SES, race/ethnicity, birth size, gestational age)
Taylor-Robinson, 2016; Prospective Cohort Study; United Kingdom (UK Millennium Cohort Study); Sample Size:; Baseline N: 14499; Analytic N: 11537; Attrition: 20%; Sample Size Calculation: NR; Sex: 49% Female; Race/Ethnicity: 88% White, 3% Mixed, 2% Indian, 4% Pakistani/ Bangladeshi, 3% Black; Atopic Disease Risk Status: 23% of mothers had asthma or eczema; Background Diet: 31% never BF, 27% BF >6mo; 55% introduced to cow’s milk <9mo | Intervention/Exposure:; Age of CFB introduction: <4, >4mo; Assessment Methods: Parent questionnaire (ISAAC); Outcomes:; Eczema; Age: 5y; Assessment Methods:; Eczema: Parent report of whether their child had ‘ever had eczema’ | Confounders:; The following confounders were accounted for: Education; Sex; Race/ethnicity; Feeding practices; Birth size; Gestational age; Smoking; Atopy risk status; Maternal age, maternal BMI, C-section, antibiotic use, dampness at home, exposure to pollution and “grime”, furry pets, siblings; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Outcome assessors were not blinded; Did not use valid/reliable measures (parent reported outcomes); Did not adjust for key confounders (SES)
Van Asperen, 1984; Prospective Cohort Study; Australia; Sample Size:; Baseline N: NR; Analytic N: 79; Attrition: Cannot determine; Sample Size Calculation: NR; Sex: NR; Race/Ethnicity: NR; Atopic Disease Risk Status: 100% had family history (parent or sibling) of atopic disease; Background Diet: 25% EBF at 4mo | Intervention/Exposure:; Age of CFB introduction: <4, >4mo; Assessment Methods: Parent interview; Outcomes:; Atopic dermatitis, allergic rhinitis; Age: 20mo; Assessment Methods:; Atopic dermatitis: Parent report of evidence of areas of scaly, erythematous, pruritic dermatitis primarily involving flexural folds, face, cheeks or areas behind the ears but excluding xeroderma alone; Allergic rhinitis: Parent report of history of nasal discharge and/or blockage occurring continuously for at least 4wk and excluding obvious infective rhinitis | Confounders:; No confounders were adjusted for; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Did not use valid/reliable measures (to assess outcomes); Did not adjust for any key confounders (Education, SES, sex, race/ethnicity, feeding practices, birth size, gestational age, smoking, atopy risk status); Limited generalizability due to exclusive enrollment of high risk subjects; Small sample size; study may have been underpowered
Venter, 2009; Prospective Cohort Study; United Kingdom; Sample Size:; Baseline N: 969; Analytic N: 927 at 3mo, 913 at 6mo, 900 at 9 and 12mo, 858 at 24mo; Attrition: 4% at 3mo, 6% at 6mo, 7% at 9 and 12mo, 12% at 24mo; Sample Size Calculation: NR; Sex: 48% Female; Race/Ethnicity: NR; Atopic Disease Risk Status: 83% had family history of allergic disease; Background Diet: BF duration: 42d, formula introduced ~14d; 27% introduced CFB <3mo, 82% <4mo, 100% by 6mo | Intervention/Exposure:; Age of CFB introduction: <4, >4mo; Assessment Methods: Parental questionnaire; Outcomes:; Food allergy; Age: 1y, 3y; Assessment Methods:; Food allergy: Parent report of symptoms, SPT wheal >3mm (milk, egg, wheat, cod, peanut, sesame), and DBPCFC | Confounders:; No confounders were adjusted for; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Did not adjust for any key confounders (Education, SES, sex, race/ethnicity, feeding practices, birth size, gestational age, smoking, atopy risk status)Small number of subjects diagnosed with food allergy; study may have been underpowered
Wilson, 1998; Prospective Cohort Study; Australia; Sample Size:; Baseline N: 674; Analytic N: 545; Attrition: 19%; Sample Size Calculation: NR; Sex: 54% Female; Race/Ethnicity: NR; Atopic Disease Risk Status: 25% had paternal history of allergic disease, 27% had maternal history of allergic disease; Background Diet: 26% EBF at 15wk, 37% partial BF at 15wk, 37% formula fed at 15wk; 73% introduced to CFB <15wk | Intervention/Exposure:; Age of CFB introduction: <15, >15wk; Assessment Methods: Parent questionnaire; Outcomes:; Asthma; Age: ~7.3y (6.1-9.9y); Assessment Methods:; Asthma: Parent report of doctor diagnosis at any time since birth (ever) or if the child was currently receiving asthma treatment (current) | Confounders:; The following confounders were accounted for: SES; Sex; Feeding practices; Birth size; Gestational age; Smoking; Atopy risk status; Weight at first solid feed; Maternal height; Maternal blood pressure; Parity; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Outcome assessors were not blinded; Did not use valid/reliable measures (to assess outcomes); Did not adjust for any key confounders (Education, race/ethnicity)
Yung, 2015; Case-Control Study; China (Hong Kong); Sample Size:; Cases: 71; Controls: 135; Attrition: NA; Sample Size Calculation: NR; Sex: 46% Female; Race/Ethnicity: NR; Atopic Disease Risk Status: 44% had parental history of atopic disease; Background Diet: 75% EBF at birth, 64% EBF at 3mo, 27% EBF at 6mo; age when solid food was introduced ~25wk | Intervention/Exposure:; Age of CFB introduction: Age in wks, continuous; Assessment Methods: Maternal questionnaire; Outcomes:; Atopic disease; Age: ~21mo (SD: 11mo) (range: 4mo-3y); Assessment Methods:; Atopy: Physician-diagnosed atopy (eczema or allergic dermatitis, asthma, rhinitis, conjunctivitis (not related to infection), and allergies (dust mite, food, drug, etc.); diagnostic methods and criteria not described | Confounders:; No confounders were adjusted for; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Did not adjust for any key confounders (Education, SES, sex, race/ethnicity, feeding practices, birth size, gestational age, smoking, atopy risk status); Cannot determine whether valid/reliable measures were used to assess outcomes; Retrospective nature of dietary recall to determine age of introduction to solid foodsSmall sample size; study may have been underpowered
Zutavern, 2006; Prospective Cohort Study; Germany (Lifestyle-Related Factors on the Immune System and the Development of Allergies in Childhood); Sample Size:; Baseline N: 3097; Analytic N: 2612; Attrition: 16%; Sample Size Calculation: NR; Sex: 48% Female; Race/Ethnicity: NR; Atopic Disease Risk Status: 53% with parental history of atopy; Background Diet: 59% EBF 4 mo, 35.7% mixed fed, 5.2 % formula fed | Intervention/Exposure:; Age of CFB introduction: 0-4, 5-6, >6mo; Assessment Methods: Parent questionnaire; Outcomes:; Atopic dermatitis; Age: 2y; Assessment Methods:; Doctor-diagnosed atopic dermatitis: Parent report of physician diagnosis of AD in the last 6mo; Symptomatic atopic dermatitis: Parent report of itching eczema within the last 6mo that was either recurrent or lasted for 2wk and that affected the skin creases, face, neck, extremities, hands, feet, or trunk (not underneath the diaper); Early skin or allergic symptoms: Parent affirmative response to, “Has a doctor diagnosed your child with 1 of the following conditions within the first 6mo of life: atopic dermatitis; allergic or atopic eczema; food allergy, hives, urticaria, or allergic edema; milk crust or seborrheic eczema; eczema without further specification?” or when parents reported an increase of eczema as a result of food intolerance within the first 6mo of their child’s life | Confounders:; The following confounders were accounted for: Education; Sex; Feeding practices; Birth size; Smoking; Atopy risk status; Study center; Number of siblings; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Outcome assessors were not blinded; Did not use valid/reliable measures to assess outcomes (parent report); Did not adjust for any key confounders (SES, race/ethnicity, gestational age, pets)
Zutavern, 2008; Prospective Cohort Study; Germany (Lifestyle-Related Factors on the Immune System and the Development of Allergies in Childhood); Sample Size:; Baseline N: 3097; Analytic N: 2073; Attrition: 33%; Sample Size Calculation: NR; Sex: 49% Female; Race/Ethnicity: NR; Atopic Disease Risk Status: 53% with parental history of atopy; Background Diet: 59% EBF at 4mo, 35.7% mixed fed, 5.2% formula fed | Intervention/Exposure:; Age of CFB introduction: <4, 4-6, >6mo; Assessment Methods: Parent questionnaire; Outcomes:; Eczema, asthma, allergic rhinitis; Age: 6y; Assessment Methods:; Atopic dermatitis: Parent report of physician diagnosis , or itching eczema within the last 6mo that was either recurrent or lasted for 2wk and that affected the skin creases, face, neck, extremities, hands, feet, or trunk (not underneath the diaper); Asthma: Parent report of physician diagnosis of asthma or report of wheezing or intake of asthma medication; Allergic rhinitis: Parent report of physician diagnosis of allergic rhinitis, or report of sneezing or a blocked or running nose without having a cold | Confounders:; The following confounders were accounted for: Education; Sex; Feeding practices; Smoking; Atopy risk status; Study center, number of siblings; Maternal age at birth; Limitations:; Cannot determine whether groups were similar at baseline on key characteristics; Outcome assessors were not blinded; Did not use valid/reliable measures to assess outcomes (parent report); Did not adjust for any key confounders (SES, race/ethnicity, gestational age, birth size, pets)

Table 2 Results from studies that examined the relationship between age of first introduction of any complementary foods and/or beverages (CFB) and food allergy, atopic dermatitis, asthma, and allergic rhinitis

Reference^1^; Study design; Country; Sample size | Age of CFB introduction | Results
FOOD ALLERGY
Grimshaw, 2013 (9); Nested Case-Control Study (Prevalence of Infant Food Allergy EuroPrevall); United Kingdom; Food Allergy Cases: 41, Controls: 82 | Age in weeks, mean | Food allergy cases vs. controls: 18wk vs 20wk; P=0.044
Grimshaw, 2013 (9); Nested Case-Control Study (Prevalence of Infant Food Allergy EuroPrevall); United Kingdom; Food Allergy Cases: 41, Controls: 82 | >17wk vs. <17wk | Food allergy at 2y: OR=0.245; 95% CI: 0.088, 0.679; P<0.05
Grimshaw, 2015 (8); Nested Case-Control Study (Prevalence of Infant Food Allergy EuroPrevall); United Kingdom; Food Allergy Cases: 41, Controls: 82 | Age in weeks, cases vs. controls | Food allergy at 2y: OR=0.506, 95% CI: 0.282, 0.908; P=0.022; Food allergy, non-IgE-mediated at 2y: OR=0.60, 95% CI: 0.40, 0.89; P=0.011; Food allergy, IgE-mediated, at 2y: No significant associations
Hesselmar, 2010 (1); Prospective Cohort Study (ALLERGY-FLORA); Sweden; N: 184 | Age in months, continuous | Food allergy at 18mo: No significant associations
Kajosaari, 1983 (2); Prospective Cohort Study; Finland; N: 135 | ~3 vs. 6mo | Food allergy at 1y: 37% vs.7%; P<0.001
Kajosaari, 1994 (3); Prospective Cohort Study; Finland; N: 135 | ~3 vs. 6mo | Food allergy at 5y: No significant associations
Luccioli, 2014 (4); Prospective Cohort Study; United States (Infant Feeding Practices Study II Year 6 Follow-Up Study); N: 1363 | 1-3/<4 vs. 4-5 vs. 6-12mo | Food allergy at 6y: No significant associations
McGowan, 2015 (5); Prospective Cohort Study (Urban Environment and Childhood Asthma Cohort); United States; N: 516 | Categories not defined | Food allergy at 5y: No significant associations
Sandini, 2011 (6); Prospective Cohort Study; Finland; N: 925 at 2y, 891 at 5y | Categories not defined | Food allergy at 2y and 5y: No significant associations
Venter, 2009 (7); Prospective Cohort Study; United Kingdom; N: 927 at 3mo, 913 at 6mo, 900 at 9 and 12mo, 858 at 24mo | <4 vs. >4mo | Food allergy at 1y: OR=0.41, 95% CI 0.18, 0.89; P=0.02; Food allergy at 3y: OR=0.51, 95% CI: 0.28, 0.92; P=0.02
ATOPIC DERMATITIS
Chuang, 2011 (10); Prospective Cohort Study; Taiwan; N: 18733 | <4, 4-6, >6mo | Atopic dermatitis at 18mo: No significant associations
Estrada-Reyes, 2007 (25); Case-Control Study; Mexico; Atopic Dermatitis Cases: 28; Controls: 28 | <6, >6mo | Atopic dermatitis, cases vs. controls: No significant associations
Fergusson, 1981 (11); Prospective Cohort Study; New Zealand; N: 1156 | <4, >4mo | Atopic dermatitis at 2y: 17.78% vs. 12.58%; P<0.05
Filipiak, 2007 (12); Prospective Cohort Study; Germany; N: 4753 | 1-4, 5-6, 7-12mo | Atopic dermatitis (doctor-diagnosed and symptomatic) at 4y: No significant associations
Forsyth, 1993 (13); Prospective Cohort Study; Scotland; N: 392 | <8, 8-12, >12wk | Atopic dermatitis between 53-104wk: 5.4% vs. 17% vs. 18%; χ2 = 7.5, P<0.05; Atopic dermatitis between 0-13, 14-26, 27-39, 40-52wk: No significant associations
Hesselmar, 2010 (1); Prospective Cohort Study; Sweden; N: 184 | Age in months, continuous | Atopic dermatitis at 18mo: No significant associations
Illi, 2004 (14); Prospective Cohort Study; Germany; N: 858 | Quartiles (not described) | Atopic dermatitis at 2y: No significant associations
Joseph, 2011 (15); Prospective Cohort Study; United States; N: 594 | <4, >4mo | Atopic dermatitis at 2-3y: No significant associations
Kajosaari, 1983 (2); Prospective Cohort Study; Finland; N: 135 | ~3, 6mo | Atopic dermatitis at 1y: 35% vs.14%; P<0.001
Kajosaari, 1994 (3); Prospective Cohort Study; Finland; N: 135 | ~3, 6mo | Atopic dermatitis at 5y: No significant associations
Mihrshahi, 2007 (16); Prospective Cohort Study; Australia; N: 516 | <3, >3mo | Atopic dermatitis at 5y: No significant associations
O’Donovan, 2016 (17); Prospective Cohort Study; United Kingdom; N: 709 | <17, >26wk | Atopic dermatitis at 12mo: No significant associations
Poysa, 1989 (18); Prospective Cohort Study; Finland; N: 70 | <3, 3-6, >6mo | Atopic dermatitis at 5y: No significant associations
Sandini, 2011 (6); Prospective Cohort Study; Finland; N: 925 at 2y, 891 at 5y | Categories not defined | Atopic dermatitis at 2y and 5y: No significant associations
Schoetzau, 2002 (19); Prospective Cohort Study; Germany; N: 1121 | 1-16, 17-24, >24wk | Atopic dermatitis at 1y: No significant associations
Snijders, 2008 (20); Prospective Cohort Study; The Netherlands; N: 2558 | <3, 4-6, >7mo | Atopic dermatitis at 2y: 3 vs 4-6mo: OR=1.28, 95% CI: 0.91, 1.81); 3 vs >7mo: OR=2.1, 95% CI: 1.17, 3.76; P=0.02; Atopic dermatitis at 2y: 3 vs 4-6mo: OR=2.67, 95% CI: 0.80, 8.97; 3 vs > 7mo: OR=9.46, 95% CI: 2.05, 43.61; P=0.00
Taylor-Robinson, 2016 (21); Prospective Cohort Study; United Kingdom; N: 11537 | <4, >4mo | Atopic dermatitis at 5y: OR=1.13, 95% CI: 1.04, 1.23
Van Asperen, 1984 (22); Prospective Cohort Study; Australia; N: 79 | <4, >4mo | Atopic dermatitis at 20mo: No significant associations
Zutavern, 2006 (23); Prospective Cohort Study; Germany; N: 2612 | 0-4, 5-6, >6mo | Atopic dermatitis at 2y: No significant associations
Zutavern, 2008 (24); Prospective Cohort Study; Germany; N: 2073 | <4, 4-6, >6mo | Atopic dermatitis at 6y: No significant associations
ASTHMA
Fergusson, 1983 (26); Prospective Cohort Study; New Zealand; N: 1110 | <4, >4mo | Asthma at 4y: No significant associations
Hetzner, 2009 (27); Prospective Cohort Study; United States; N: 7900 | <6, >6mo | Asthma at 2y: No significant associations
Kajosaari, 1994 (3); Prospective Cohort Study; Finland; N: 135 | ~3, 6mo | Asthma at 5y: No significant associations
Mihrshahi, 2007 (16); Prospective Cohort Study; Australia; N: 516 | <3, >3mo | Asthma at 5y: No significant associations
Nathan, 2012 (28); Case-Control Study; Malaysia; Asthma Cases: 78, Controls: 78 | <6, >6mo | Asthma cases vs.controls: 65% vs. 33%; P<0.001
Sandini, 2011 (6); Prospective Cohort Study; Finland; N: 925 at 2y, 891 at 5y | Categories not defined | Asthma at 2y and 5y: No significant associations
Wilson, 1998 (29); Prospective Cohort Study; Australia; N: 545 | : <15, >15wk | Asthma at ~7y: No significant associations
Zutavern, 2008 (24); Prospective Cohort Study; Germany; N: 2073 | <4, 4-6, >6mo | Asthma at 6y: No significant associations
ALLERGIC RHINITIS
Kajosaari, 1994 (3); Prospective Cohort Study; Finland; N: 135 | ~3, 6mo | Allergic rhinitis at 5y: 37% vs. 20%; P=0.04
Sandini, 2011 (6); Prospective Cohort Study; Finland; N: 925 at 2y, 891 at 5y | Categories not defined | Allergic rhinitis at 2y and 5y: No significant associations
Van Asperen, 1984 (22); Prospective Cohort Study; Australia; N: 79 | <4, >4mo | Allergic rhinitis at 20mo: No significant associations
Zutavern, 2008 (24); Prospective Cohort Study; Germany; N: 2073 | <4, 4-6, >6mo | Allergic rhinitis at 6y: No significant associations
ATOPIC DISEASE
Kajosaari, 1994 (3); Prospective Cohort Study; Finland; N: 135 | ~3, 6mo | Atopic disease at 5y: No significant associations
Poysa, 1991 (30); Prospective Cohort Study; Finland; N: 68 | <3, 3-6, >6mo | Atopic disease at 9y: No significant associations
Yung, 2015 (31); Case-Control Study; China (Hong Kong); Atopic Cases: 71, Controls: 135 | Categories not defined | Atopic disease, cases vs. controls: No significant associations

1 References may be repeated if reporting multiple different outcomes in relation to the age when complementary feeding began

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The analytic framework in Figure 1 is for systematic reviews conducted to examine the relationship between complementary feeding and food allergy, atopic dermatitis/eczema, asthma, and allergic rhinitis

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts all contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on complementary feeding and food allergy, atopic dermatitis/eczema, asthma, and allergic rhinitis. For this systematic review, the target population considered was generally health infants. The interventions or exposures considered was timing or type and amount of complementary foods and beverages consumed and their comparators were different timing or types and amounts. The outcomes considered were food allergy, atopic dermatitis/eczema, asthma, or allergic rhinitis. The key confounders were education, socioeconomic status, sex, race and/or ethnicity, milk feeding practicies, birth size, gestational age, cigarette smoke exposure, atopic disease risk status, and household pets.

## SEARCH PLAN AND RESULTS

### Inclusion and exclusion criteria

The inclusion and exclusion criteria are a set of characteristics to determine which studies will be included or excluded in the systematic review. This table provides the inclusion and exclusion criteria for the systematic review question(s): What is the relationship between timing of introduction of complementary foods/beverages or types and amounts of complementary foods/beverages and food allergy, atopic dermatitis/eczema, asthma, and allergic rhinitis?

Table 3 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | Randomized controlled trials | Cross-sectional studies
Study design | Non-randomized controlled trials | Uncontrolled studies
Study design | Prospective cohort studies | Pre/post studies without a control
Study design | Retrospective cohort studies | Narrative reviews
Study design | Case-control studies | Systematic reviews
Study design | Pre/post studies with a control | Meta-analyses
Independent variable (intervention or exposure) | Timing of introduction to complementary foods and beverages (CFB) (i.e., foods and beverages (liquids, semisolids, and solids) other than human milk or infant formula provided to an infant or young child to provide nutrients and energy) | Consumption of fluid cow’s milk before 12 months of age
Independent variable (intervention or exposure) | Types or amounts of CFB
Comparator | Different timing of introduction of CFB
Comparator | Different types and amounts of CFB
Dependent variables (outcomes) | Incidence, prevalence, and/or severity of: food allergy, atopic dermatitis/eczema, asthma, and/or allergic rhinitis | Food allergy when diagnosis was based solely on food allergen sensitization (i.e., skin prick test, or serum IgE measure)
Dependent variables (outcomes) | | Asthma when diagnosis was based solely on report of wheeze
Date range | January 1980 – February 2017
Language | Studies published in English | Studies published in languages other than English
Publication status | Studies published in peer-reviewed journals | Grey literature, including unpublished data, manuscripts, reports, abstracts, conference proceedings
Country^1,^ ^2,^ ^3^ | Studies conducted in Very High or High Human Development Countries | Studies conducted in Medium or Low Human Development Countries
Study participants | Human subjects | Hospitalized patients, not including birth and immediate post-partum hospitalization of healthy babies
Study participants | Males
Study participants | Females
Age of study participants | Age at intervention or exposure: Infants (0-12mo); Toddlers (12-24mo) | Age at intervention or exposure: Child (2-5 years (y)); Child (6-12y); Adolescents (13-18y); Adults (19y and older); Older adults (65 to 79y); Older adults (80+y)
Age of study participants | Age at outcome: Infants (0-12mo; food allergy, atopic dermatitis, allergic rhinitis); Toddlers (12-24mo; food allergy, atopic dermatitis, allergic rhinitis); Child (2-5 years (y)); Child (6-12y); Adolescents (13-18y) | Age at outcome: Infants (0-12 months) (asthma); Toddlers (12-24 months) (asthma); Adults (19y and older); Older adults (65 to 79y); Older adults (80+y)
Health status of study participants | Studies done in generally healthy populations | Studies that exclusively enroll subjects with a disease or with the health outcome of interest
Health status of study participants | Studies done in populations where infants were full term (≥37wk gestational age) | Studies done in hospitalized or malnourished subjects
Health status of study participants | Studies done in populations with elevated chronic disease risk, or that enroll some participants with a disease or with the health outcome of interest | Studies of exclusively pre-term babies (gestational age <37wk) or babies that are small for gestational age (<2500g)
Health status of study participants | | Studies of subjects with infectious diseases (e.g. HIV/AIDS) (or with mothers diagnosed with an infectious disease)

1 United Nations Development Programme. Human Development Report 2014: Reducing Vulnerabilities and Building Resilience. Available from: http://hdr.undp.org/en/content/human-development-report-2014 . (32)

2 Medium Development Countries were originally included, but due to concerns about generalizability to the U.S. of study participants (i.e., baseline health status) and CFB typically consumed, a decision was made to exclude “Medium” countries in October 2017.

3 When a country was not included in the Human Development Report 2014, country classification from the World Bank was used instead. (33)

### Search terms and electronic databases used

#### PubMed, US National Library of Medicine (https://www.nlm.nih.gov/bsd/medline.html) (1966 to 8 February 2017)

Date(s) Searched: 2/8/2017

Search Terms:

Date range searched: 1980-2/8/17

(Complementary OR supplementary OR wean* OR transition* OR introduc* OR “Infant Nutritional Physiological Phenomena”[Mesh:noexp] OR weaning[mesh] OR bottle*)

AND (feeding* OR food* OR beverage*[tiab] OR beverages[mh] OR eating OR diet[tiab] OR diet[mh] OR meal*[tiab] OR meals[mh] OR “Food and Beverages”[Mesh] OR diets[tiab] OR cereal*[tiab] OR “Edible Grain”[Mesh] OR bread*[tiab] OR whole grain* OR juice*[tiab] OR milk[tiab] OR “Milk”[Mesh] OR dairy[tiab] OR “Dairy Products”[Mesh] OR meat[tiab] OR cheese[tiab] OR yogurt[tiab] OR yoghurt*[tiab] OR fruit*[tiab] OR “Fruit”[Mesh] OR vegetable*[tiab] OR “Vegetables”[Mesh] OR egg*[tiab] OR “Eggs”[Mesh] OR nut[tiab] OR nuts[tiab] OR peas[tiab] OR beans[tiab] OR legume*[tiab] OR snack*[tiab] OR bread[mh] OR honey[mh] OR vegetable*[tiab] OR “Vegetables”[Mesh] OR egg*[tiab] OR “Eggs”[Mesh:noexp] OR “egg white”[mh] OR “egg yolk”[mh] OR snack*[tiab] OR candy[mh] OR “Fast Foods”[Mesh] OR meat[mh] OR molasses[mh] OR nuts[mh] OR “Raw Foods”[Mesh] OR seeds[mh])

OR

“infant food”[mesh] OR infant feed* OR Bottle feeding[mh] OR bottle feeding*[tiab] OR bottle feeding OR bottle-feeding*[tiab] OR bottle-feedings OR bottle-fed[tiab] OR “bottle fed”[tiab] OR solid food*

AND

NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic[sb])

(“Study Characteristics” [Publication Type] OR “clinical trial”[ptyp] OR “Epidemiologic Studies”[Mesh] OR “Support of Research”[ptyp] OR cohort[tiab] OR observational[tiab] OR retrospective[tiab] OR longitudinal[tiab] OR trial[tiab] OR trials[tiab] OR case control*[tiab] OR case-control*[tiab] OR before-after stud*[tiab] OR before after stud*[tiab]

(includes age filter: Filters: Infant: birth-23 months and preschool child 2-5 yrs)

OR ((Solid food*) OR solids))

AND

((“Allergy and Immunology”[Mesh:NoExp] OR allergy[tiab] OR allergies[tiab] OR allergic[tiab] OR Hypersensitivit*[tiab]) AND (food OR peanut* OR nut OR nuts OR egg OR eggs OR milk OR shellfish OR wheat)) OR “Food Hypersensitivity”[Mesh] OR asthma OR “Rhinitis, Allergic”[Mesh] OR (allergic[tiab] AND Rhiniti*[tiab]) OR “Dermatitis, Atopic”[Mesh] OR ((Dermatiti*[tiab] OR eczema[tiab]) AND Atopic[tiab]) OR (Infant* AND Eczema) OR “Immunoglobulin E”[Mesh] OR “Immunoglobulin E”[tiab] OR IgE[tiab]

for nonmedline[sb]: NOT animals by: NOT (sheep[ti] OR lamb[ti] OR lambs[ti] OR calving[ti] OR calves[ti] OR mice[ti] OR mouse[ti] OR pigs[ti] OR cows[ti] OR piglets[ti] OR cow[ti] OR piglet[ti] OR monkey[ti] OR rats[ti] OR rat[ti] OR animal*[ti])

infant* OR baby OR babies OR toddler* OR newborn*[tiab] OR “Child, Preschool”[Mesh] OR preschool*[tiab] OR pre-school*[tiab] OR “early childhood”[tiab] OR early year*[tiab] OR pre-k[tiab] OR pre-primary[tiab] OR under five*[ti] OR young child*[ti] OR prekindergarten[tiab] OR pre-kindergarten[tiab] OR weanling* OR “first two years” OR “first 2 years”

#### Embase, Elsevier (https://www.elsevier.com/solutions/embase-biomedical-research/embase-coverage-and-content) (1947 to February 2017)

Date(s) Searched: 2/2017

Search Terms:

‘complementary feeding’/exp OR

(Complementary OR supplementa* OR wean* OR transition* OR introduc* OR family) NEAR/3 (feed* OR food* OR beverage* OR eating OR diet)

OR

(Complementary OR transition* OR introduct* OR wean*) AND (food/exp OR ‘baby food’/exp OR ‘cereal’/exp OR ‘dairy product’/exp OR ‘egg’/exp OR ‘fruit’/exp OR ‘meat’/exp OR ‘sea food’/exp OR ‘milk’/exp OR fish/exp OR ‘poultry’/exp OR ‘beverage’/exp OR ‘vegetable’/exp OR nut/exp OR pea/exp OR meal/exp OR ‘infant feeding’/exp)

OR

(Complementary OR supplementa* OR wean* OR transition* OR introduc*) NEAR/5 (‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR beverage* OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR bread* OR yog*urt* OR cheese* OR juice* OR rice OR soup OR legume* OR snack* OR meal*)

OR ‘baby food’/de OR (solid NEAR/2 food*):ab,ti

AND

(infant*:ti,ab OR infant/exp) OR (baby OR babies OR toddler* OR newborn* OR nurser*):ti,ab OR ‘newborn’/exp OR ‘newborn care’/exp OR preschool*:ti,ab OR preschool:ti,ab OR ‘pre-school child’/exp OR ‘infancy’/exp OR “early childhood”:ti,ab OR “early years” OR pre-k:ti,ab OR ‘nursery’/exp OR ‘nursery school’/exp OR prekindergarten:ti,ab OR pre-kindergarten:ti,ab OR weanling* (includes limits below) OR ([newborn]/lim OR [infant]/lim OR [child]/lim OR [preschool]/lim)

AND ([in process]/lim OR [article]/lim OR [article in press]/lim) AND ([embase]/lim NOT [medline]/lim)

Limit to humans:

AND

‘allergic asthma’/exp OR ‘food allergy’/exp OR ‘allergic rhinitis’/exp OR ‘dermatitis’/exp OR ‘eczema’/exp OR ‘skin allergy’/exp OR ((allerg* OR hypersensitivity*) NEAR/3 (food OR peanut* OR nut OR nuts OR egg OR milk OR shellfish OR wheat)) OR ‘immunoglobulin E’/exp OR ‘immunoglobulin E’:ti,ab OR ‘atopy’/exp OR atopy:ti,ab OR atopic:ti,ab OR IgE:ti,ab

#### Cochrane Central Register of Controlled Trials (https://handbook-5-1.cochrane.org/chapter_6/6_2_1_2_the_cochrane_central_register_of_controlled_trials.htm), John Wiley & Sons in the Cochrane Library (searched 9 February 2017)

Date(s) Searched: 2/9/17

Search Terms:

(feed* OR food* OR beverage*OR diet* OR ‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR beans OR legume* OR nut OR cereal OR beverage* OR bread* OR seafood OR yog*urt* OR cheese OR juice OR snack OR yogurt OR yoghurt OR nut OR nuts OR honey OR meal OR meals) NEAR/3 (Complementary OR supplementa* OR wean* OR transition* OR introduct* OR family)

OR

[mh ^“Infant Nutritional Physiological Phenomena”] OR [mh weaning] OR ((bottle*) NOT (milk OR formula))

AND ([mh beverages] OR [mh eating] OR [mh diet] OR [mh meals] OR [mh “Food and Beverages”] OR [mh “Edible Grain”] OR [mh “Milk”] OR dairy:ti,ab OR [mh “Dairy Products”] OR [mh “Fruit”] OR [mh “Vegetables”] OR [mh “Eggs”] OR [mh bread] OR [mh honey] OR [mh “Vegetables”] OR [mh ^“Eggs”] OR [mh “egg white”] OR [mh “egg yolk”] OR [mh candy] OR [mh “Fast Foods”] OR [mh meat] OR [mh molasses] OR [mh nuts] OR [mh “Raw Foods”] OR [mh seeds])

OR

((Infant* OR baby* OR babies) NEAR/2 food*):ti,ab OR [mh “infant food”]

AND

[mh ^“Allergy and Immunology”] OR ((allerg*:ti,ab OR Hypersensitivit*:ti,ab) AND (food OR peanut OR nut OR nuts OR egg OR milk OR shellfish OR wheat)) OR [mh “Food Hypersensitivity”] OR asthma* OR [mh” Rhinitis, Allergic”] OR (allerg* NEAR/5 Rhiniti*) OR [mh “Dermatitis, Atopic”] OR ((Dermatiti* OR eczema) NEAR/5 Atopic) OR (Infant* NEAR/5 Eczema) OR [mh “Immunoglobulin E”] OR “Immunoglobulin E”:ti,ab OR IgE:ti,ab

#### CINAHL Plus with Full Text, EBSCO (https://www.ebsco.com/products/research-databases/cinahl-plus-full-text) (Cumulative Index to Nursing and Allied Health Literature; 1937 to 9 February 2017)

Date(s) Searched: 2/9/17

Search Terms:

209; selected 26 for downloading

(MH “Food Hypersensitivity+”) OR (MH “Milk Hypersensitivity”) OR (MH “Pollen-Food Allergy”) OR (MH “Rhinitis, Atrophic”) OR “Immunoglobulin e” OR (MH “Eczema”) OR (MH “Dermatitis, Atopic”)

AND

(MH “Food and Beverages+”) OR (MH “Food”) OR (MH “Diet”) OR (MH “Eating”) OR (MH “Eating Behavior”) OR (MH “Taste”) OR (MH “Taste Buds”) OR (MH “Cereals”) OR (MH “Dairy Products”) OR (MH “Yogurt”) OR (MH “Cheese”) OR (MH “Milk”) OR (MH “Eggs”) OR (MH “Fruit”) OR (MH “Fruit Juices”) OR (MH “Meat”) OR (MH “Seafood”) OR (MH “Fish”) OR (MH “Poultry”) OR (MH “Vegetables”) OR (MH “Nuts”) OR (MH “Legumes”) OR (MH “Bread”) AND (Complementary OR supplementa* OR wean* OR transition* OR introduc*)

OR

(‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR beverage* OR bread* OR seafood OR yog*urt* OR cheese* OR juice*) N5 (Complementary OR supplementa* OR wean* OR transition* OR introduc* OR family)

OR (Infant* OR baby OR babies) N3 food*

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between complementary feeding and food allergy, atopic dermatitis/eczema, asthma, and allergic rhinitis. The results of the electronic database searches were screened independently by two NESR analysts in a step-wise manner by reviewing titles, abstracts, and full text articles to determine which articles met the criteria for inclusion. A manual search was done to ascertain articles not identified through the electronic database search. The systematic review on timing of CFB introduction included 31 articles, and the systematic review on on types and amounts of CFB consumed included 47 articles.

This flow chart illustrates the literature search and screening results for articles examining the relationship between complementary feeding and food allergy, atopic dermatitis/eczema, asthma, and allergic rhinitis. The results of the electronic database searches were screened independently by two NESR analysts in a step-wise manner by reviewing titles, abstracts, and full text articles to determine which articles met the criteria for inclusion. A manual search was done to ascertain articles not identified through the electronic database search. The systematic review on timing of CFB introduction included 31 articles, and the systematic review on on types and amounts of CFB consumed included 47 articles.

### Excluded articles

The table below lists the excluded articles with at least one reason for exclusion, and may not reflect all possible reasons.

Table 4 Excluded articles

| Citation | Reasons for Exclusion
1 | Children’s peanut allergies arising at younger ages. AORN Journal. 2008;87:624-624. | Study design
2 | Infants with food protein allergy tolerate soy milk earlier than cow’s. Community Practitioner. 2009;82:41-41. | Study design
3 | Significance of food hypersensitivity in children with atopic dermatitis. Pediatr Dermatol. 1986;3:161-74. | Study design
4 | Aberg, N.,Engstrom, I.,Lindberg, U.. Allergic diseases in Swedish school children. Acta Paediatr Scand. 1989;78:246-52. | Study design
5 | Abrams, E. M.,Becker, A. B.. Introducing solid food: age of introduction and its effect on risk of food allergy and other atopic diseases. Can Fam Physician. 2013;59:721-2. | Study design
6 | Alper, Z.,Sapan, N.,Ercan, I.,Canitez, Y.,Bilgel, N.. Risk factors for wheezing in primary school children in Bursa, Turkey. Am J Rhinol. 2006;20:53-63. | Study design
7 | Armentia, A.,Rodriguez, R.,Callejo, A.,Martin-Esteban, M.,Martin-Santos, J. M.,Salcedo, G.,Pascual, C.,Sanchez-Monge, R.,Pardo, M.. Allergy after ingestion or inhalation of cereals involves similar allergens in different ages. Clin Exp Allergy. 2002;32:1216-22. | Health Status, Independent Variable
8 | Arshad, S. H.,Matthews, S.,Gant, C.,Hide, D. W.. Effect of allergen avoidance on development of allergic disorders in infancy. Lancet. 1992;339:1493-7. | Independent Variable
9 | Bardara, M.,Varin, E.,Zani, G.. Response to diet in 130 children affected with atopic dermatitis. Allergy. 1989:147-50. | Study design
10 | Bardare, M.,Vaccari, A.,Allievi, E.,Brunelli, L.,Coco, F.,de Gaspari, G. C.,Flauto, U.. Influence of dietary manipulation on incidence of atopic disease in infants at risk. Ann Allergy. 1993;71:366-71. | Independent Variable
11 | Becker, A.,Watson, W.,Ferguson, A.,Dimich-Ward, H.,Chan-Yeung, M.. The Canadian asthma primary prevention study: outcomes at 2 years of age. J Allergy Clin Immunol. 2004;113:650-6. | Study design, Independent Variable
12 | Benn, C. S.,Wohlfahrt, J.,Aaby, P.,Westergaard, T.,Benfeldt, E.,Michaelsen, K. F.,Bjorksten, B.,Melbye, M.. Breastfeeding and risk of atopic dermatitis, by parental history of allergy, during the first 18 months of life. Am J Epidemiol. 2004;160:217-23. | Independent Variable
13 | Berg, Av,Kramer, U.,Link, E.,Bollrath, C.,Heinrich, J.,Brockow, I.,Koletzko, S.,Grubl, A.,Filipiak-Pittroff, B.,Wichmann, H. E.,Bauer, C. P.,Reinhardt, D.,Berdel, D.. Impact of early feeding on childhood eczema: development after nutritional intervention compared with the natural course - the GINIplus study up to the age of 6 years. Clin Exp Allergy. 2010;40:627-36. | Independent Variable
14 | Bergmann, R. L.,Bergmann, K. E.,Lau-Schadensdorf, S.,Luck, W.,Dannemann, A.,Bauer, C. P.,Dorsch, W.,Forster, J.,Schmidt, E.,Schulz, J.,et, al. Atopic diseases in infancy. The German multicenter atopy study (MAS-90). Pediatr Allergy Immunol. 1994;5:19-25. | Independent Variable
15 | Bilenko, N.,Ghosh, R.,Levy, A.,Deckelbaum, R. J.,Fraser, D.. Partial breastfeeding protects Bedouin infants from infection and morbidity: prospective cohort study. Asia Pac J Clin Nutr. 2008;17:243-9. | Independent Variable
16 | Bion, V.,Lockett, G. A.,Soto-Ramírez, N.,Zhang, H.,Venter, C.,Karmaus, W.,Holloway, J. W.,Arshad, S. H.. Evaluating the efficacy of breastfeeding guidelines on long-term outcomes for allergic disease. Allergy: European Journal of Allergy and Clinical Immunology. 2016;71:661-670. | Independent Variable
17 | Birkbeck, J. A.. Goat milk in infant nutrition. N Z Med J. 1984;97:413-4. | Study design
18 | Blumberg, S.. Infant feeding: can we spice it up a bit?. J Am Diet Assoc. 2006;106:504-5. | Study design
19 | Bruno, G.,Milita, O.,Ferrara, M.,Nisini, R.,Cantani, A.,Businco, L.. Prevention of atopic diseases in high risk babies (long-term follow-up). Allergy Proc. 1993;14. | Independent Variable
20 | Burks, K.,Jones, S.. The Canadian asthma primary prevention study: Outcomes at 2 years of age. Pediatrics. 2005;116:537-4005. | Study design
21 | Burr, M. L.,Limb, E. S.,Maguire, M. J.,Amarah, L.,Eldridge, B. A.,Layzell, J. C.,Merrett, T. G.. Infant feeding, wheezing, and allergy: a prospective study. Arch Dis Child. 1993;68:724-8. | Independent Variable
22 | Burr, M. L.,Merrett, T. G.,Dunstan, F. D.,Maguire, M. J.. The development of allergy in high-risk children. Clin Exp Allergy. 1997;27:1247-53. | Independent Variable
23 | Calamaro, C. J.. Infant nutrition in the first year of life: tradition or science?. Pediatr Nurs. 2000;26:211-5. | Study design
24 | Cant, A. J.,Bailes, J. A.. How should we feed the potentially allergic infant?. Hum Nutr Appl Nutr. 1984;38:474-6. | Study design
25 | Challacombe, D. N.. Allergies and infant feeding. Midwife Health Visit Community Nurse. 1986;22:164-6. | Study design
26 | Chandra, R. K.. Role of maternal diet and mode of infant feeding in prevention of atopic dermatitis in high risk infants. Allergy. 1989:135-9. | Study design
27 | Chiu, C. Y.,Liao, S. L.,Su, K. W.,Tsai, M. H.,Hua, M. C.,Lai, S. H.,Chen, L. C.,Yao, T. C.,Yeh, K. W.,Huang, J. L.. Exclusive or Partial Breastfeeding for 6 Months Is Associated with Reduced Milk Sensitization and Risk of Eczema in Early Childhood. Medicine (United States). 2016;95. | Independent Variable
28 | Cho, H. N.,Hong, S.,Lee, S. H.,Yum, H. Y.. Nutritional status according to sensitized food allergens in children with atopic dermatitis. Allergy Asthma Immunol Res. 2011;3:53-7. | Study design
29 | Cudowska, B.,Marcinkiewicz, S.,Kaczmarski, M.. Sensitization to cereal allergens in children with atopic dermatitis. Postepy Dermatologii i Alergologii. 2011;28:181-186. | Study design, Health Status
30 | de Looy, A. E.. Infant nutrition. Nursing (Lond). 1986;3:446-9. | Study design
31 | del-Rio Camacho, G.,Martinez Jimenez, V.,Fernandez-Cantalejo Padial, J.. Absence of clinical symptoms upon introduction of egg into the diet of milk-allergic infants not previously sensitised to egg. Allergol Immunopathol (Madr). 2012;40:374-8. | Health Status, Independent Variable
32 | Dieguez, M. C.,Cerecedo, I.,Muriel, A.,Zamora, J.,Sanchez-Cano, M.,De la Hoz, B.. Skin prick test predictive value on the outcome of a first known egg exposure in milk-allergic children. Pediatr Allergy Immunol. 2008;19:319-24. | Health Status, Independent Variable
33 | Du Toit, G.,Katz, Y.,Sasieni, P.,Mesher, D.,Maleki, S. J.,Fisher, H. R.,Fox, A. T.,Turcanu, V.,Amir, T.,Zadik-Mnuhin, G.,Cohen, A.,Livne, I.,Lack, G.. Early consumption of peanuts in infancy is associated with a low prevalence of peanut allergy. J Allergy Clin Immunol. 2008;122:984-91. | Study design, Dependent Variable
34 | Dubakiene, R.,Rudzeviciene, O.,Butiene, I.,Sezaite, I.,Petronyte, M.,Vaicekauskaite, D.,Zvirbliene, A.. Studies on early allergic sensitization in the Lithuanian birth cohort. ScientificWorldJournal. 2012;2012:909524. | Independent Variable
35 | Duczmal, E.,Breborowicz, A.,Duczmal, T.. The influence of specific factors on the prevalence of allergic diseases in a birth cohort study [polish]. Alergia Astma Immunologia. 2011;16:96-104. | Language
36 | Dunlop, A. L.,Reichrtova, E.,Palcovicova, L.,Ciznar, P.,Adamcakova-Dodd, A.,Smith, S. J.,McNabb, S. J.. Environmental and dietary risk factors for infantile atopic eczema among a Slovak birth cohort. Pediatr Allergy Immunol. 2006;17:103-11. | Study design
37 | Early peanut consumption may prevent allergy. Nurse Prescribing. 2008;6:509-509. | Study design
38 | Exl, B. M.,Deland, U.,Secretin, M. C.,Preysch, U.,Wall, M.,Shmerling, D. H.. Improved general health status in an unselected infant population following an allergen-reduced dietary intervention programme: the ZUFF-STUDY-PROGRAMME. Part II: infant growth and health status to age 6 months. ZUg-FrauenFeld. Eur J Nutr. 2000;39:145-56. | Independent Variable
39 | Fadeeva, T.,Asin, J. L.,Horrillo, M. L.,Baraut, T. G.,Vela, R. F.,Conde, S. L.,Hontoria, O. E.,Valero, C. B.,Molina, A. M.. Results of the oral egg-challenge test performed on two different groups of children. One group with a history, suggestive of allergic reaction with egg intake and the other group sensitised to hen’s egg without previous egg intake. Allergol Immunopathol (Madr). 2010;38:233-40. | Independent Variable
40 | Filipiak, B.,Zutavern, A.,Koletzko, S.,Von Berg, A.,Brockow, I.,Grübl, A.,Berdel, D.,Reinhardt, D.,Bauer, C. P.,Wichmann, H. E.,Heinrich, J.. Early solid food introduction and development of eczema in the first 4 years. Results from the GINI birth cohort. Allergo Journal. 2008;17:82-83. | Language
41 | Fiocchi, A.,Verga, M. C.. Early allergenic-food introduction does not reduce subsequent food allergy development. J Pediatr. 2016;178:305-306. | Study design
42 | Flohr, C.,Nagel, G.,Weinmayr, G.,Kleiner, A.,Strachan, D. P.,Williams, H. C.. Lack of evidence for a protective effect of prolonged breastfeeding on childhood eczema: lessons from the International Study of Asthma and Allergies in Childhood (ISAAC) Phase Two. Br J Dermatol. 2011;165:1280-9. | Study design
43 | Frank, L.,Marian, A.,Visser, M.,Weinberg, E.,Potter, P. C.. Exposure to peanuts in utero and in infancy and the development of sensitization to peanut allergens in young children. Pediatr Allergy Immunol. 1999;10:27-32. | Country
44 | Gabet, S.,Just, J.,Couderc, R.,Seta, N.,Momas, I.. Allergic sensitisation in early childhood: Patterns and related factors in PARIS birth cohort. Int J Hyg Environ Health. 2016;219:792-800. | Dependent Variable
45 | Geller-Bernstein, G.,Kenett, R.,Weisglass, L.,Tsur, S.,Lahav, M.,Levin, S.. Atopic babies with wheezy bronchitis. Follow-up study relating prognosis to sequential IgE values, type of early infant feeding, exposure to parental smoking and incidence of lower respiratory tract infections. Allergy. 1987;42:85-91. | Health Status, Independent Variable
46 | Ghaderi, R.,Makhmalbaf, Z.. Effect of breast-feeding on the development of atopic dermatitis. Iranian Journal of Allergy, Asthma and Immunology. 2005;4:129-132. | Independent Variable
47 | Ghadi, A.,Dutau, G.,Rancé, F.. A sensitization study of atopic children in Marrakech. A prospective study of 160 children between 2002 and 2005 [french]. Revue Francaise d’Allergologie et d’Immunologie Clinique. 2007;47:409-415. | Language
48 | Gray, C. L.,Levin, M. E.,du Toit, G.. Patterns of introduction of solids in South African children with atopic dermatitis: Do they affect allergy rates?. Current Allergy and Clinical Immunology. 2014;27:334-336. | Study design, Health Status
49 | Greenhawt, M.,Venter, C.. Having your cake and EATing it too: early timing of multiple allergen introduction does not increase the risk of developing food allergy in standard risk, breastfed infants. Evid Based Med. 2017. | Study design
50 | Greenhawt, M.. Early Allergen Introduction for Preventing Development of Food Allergy [editorial]. Jama. 2016;316:1157-1159. | Study design
51 | Greenhawt, M.. Early Allergen Introduction for Preventing Development of Food Allergy. Jama. 2016;316:1157-1159. | Study design
52 | Guilbert, T. W.,Stern, D. A.,Morgan, W. J.,Martinez, F. D.,Wright, A. L.. Effect of breastfeeding on lung function in childhood and modulation by maternal asthma and atopy. Am J Respir Crit Care Med. 2007;176:843-8. | Independent Variable
53 | Gupta, R. S.,Walkner, M. M.,Greenhawt, M.,Lau, C. H.,Caruso, D.,Wang, X.,Pongracic, J. A.,Smith, B.. Food Allergy Sensitization and Presentation in Siblings of Food Allergic Children. Journal of Allergy and Clinical Immunology: In Practice. 2016;4:956-962. | Health Status, Independent Variable
54 | Halken, S.,Host, A.,Hansen, L. G.,Osterballe, O.. Effect of an allergy prevention programme on incidence of atopic symptoms in infancy. A prospective study of 159 “high-risk” infants. Allergy. 1992;47:545-53. | Independent Variable
55 | Halken, S.. What causes allergy and asthma? The role of dietary factors. Pediatr Pulmonol Suppl. 2004;26:223-4. | Study design
56 | Hartman, H.,Dodd, C.,Rao, M.,DeBlasio, D.,Labowsky, C.,D’Souza, S.,Lenkauskas, S.,Roeser, E.,Heffernan, A.,Assa’ad, A.. Parental timing of allergenic food introduction in urban and suburban populations. Ann Allergy Asthma Immunol. 2016;117. | Dependent Variable
57 | Hill, D. J.,Hosking, C. S.. Preventing childhood allergy. Med J Aust. 1993;158:367-9. | Study design
58 | Holmes, S.. Planning for the best start in life. A guide to infant feeding. Prof Nurse. 1991;6:200-5. | Study design
59 | Hon, K. L. E.,Tsang, Y. C.,Poon, T. C. W.,Pong, N. H. H.,Luk, N. M.,Leung, T. N. H.,Chow, C. M.,Leung, T. F.. Dairy and nondairy beverage consumption for childhood atopic eczema: What health advice to give?. Clinical and Experimental Dermatology. 2016;41:129-137. | Study design, Age
60 | Horwitz, A. A.,Hossain, J.,Yousef, E.. Correlates of outcome for atopic dermatitis. Ann Allergy Asthma Immunol. 2009;103:146-51. | Study design, Health Status
61 | Howie, P. W.,Forsyth, J. S.,Ogston, S. A.,Clark, A.,Florey, C. D.. Protective effect of breast feeding against infection. Bmj. 1990;300:11-6. | Independent Variable
62 | Hua, M. C.,Chen, C. C.,Liao, S. L.,Yao, T. C.,Tsai, M. H.,Lai, S. H.,Chiu, C. Y.,Yeh, K. W.,Huang, J. L.. Faecal eosinophil cationic protein and serum immunoglobulin E in relation to infant feeding practices. Ann Clin Biochem. 2016. | Dependent Variable
63 | Ito, J.,Fujiwara, T.. Breastfeeding and risk of atopic dermatitis up to the age 42 months: a birth cohort study in Japan. Ann Epidemiol. 2014;24:267-72. | Independent Variable
64 | Juto, P.,Bjorksten, B.. Serum IgE in infants and influence of type of feeding. Clin Allergy. 1980;10:593-600. | Independent Variable
65 | Juto, P.,Moller, C.,Engberg, S.,Bjorksten, B.. Influence of type of feeding on lymphocyte function and development of infantile allergy. Clin Allergy. 1982;12:409-16. | Independent Variable
66 | Kajosaari, M.. Atopy prophylaxis in high-risk infants. Prospective 5-year follow-up study of children with six months exclusive breastfeeding and solid food elimination (not peer review). Adv Exp Med Biol. 1991;310:453-8. | Study design
67 | Kaufman, H. S.,Frick, O. L.. Prevention of asthma. Clin Allergy. 1981;11:549-53. | Independent Variable
68 | Khoo, P.,Boyce, S.. Does early introduction of allergenic foods decrease the risk of food allergies?. J Paediatr Child Health. 2016;52:850. | Study design
69 | Kiefte-de Jong, J. C.,de Vries, J. H.,Franco, O. H.,Jaddoe, V. W.,Hofman, A.,Raat, H.,de Jongste, J. C.,Moll, H. A.. Fish consumption in infancy and asthma-like symptoms at preschool age. Pediatrics. 2012;130:1060-8. | Dependent Variable
70 | Kiefte-de Jong, J. C.,Escher, J. C.,Arends, L. R.,Jaddoe, V. W.,Hofman, A.,Raat, H.,Moll, H. A.. Infant nutritional factors and functional constipation in childhood: the Generation R study. Am J Gastroenterol. 2010;105:940-5. | Dependent Variable
71 | Kim, J.,Chung, Y.,Han, Y.,Ahn, K.,Lee, S. I.. The natural history and prognostic factors of egg allergy in Korean infants with atopic dermatitis. Asian Pac J Allergy Immunol. 2009;27:107-14. | Health Status
72 | Kmietowicz, Zosia. Risk of peanut allergy can be reduced by 80% by including peanuts in infant diets. BMJ: British Medical Journal. 2015;350. | Study design
73 | Koletzko, B.. Complementary foods and the development of food allergy. Pediatrics. 2000;106:1285. | Study design
74 | Koletzko, S.. 2.5 Allergy Prevention through Early Nutrition. World Rev Nutr Diet. 2015;113:113-7. | Study design
75 | Koplin, J. J.,Osborne, N. J.,Wake, M.,Martin, P. E.,Gurrin, L. C.,Robinson, M. N.,Tey, D.,Slaa, M.,Thiele, L.,Miles, L.,Anderson, D.,Tan, T.,Dang, T. D.,Hill, D. J.,Lowe, A. J.,Matheson, M. C.,Ponsonby, A. L.,Tang, M. L.,Dharmage, S. C.,Allen, K. J.. Can early introduction of egg prevent egg allergy in infants? A population-based study. J Allergy Clin Immunol. 2010;126:807-13. | Study design, Independent Variable
76 | Koplin, J.,Dharmage, S. C.,Gurrin, L.,Osborne, N.,Tang, M. L.,Lowe, A. J.,Hosking, C.,Hill, D.,Allen, K. J.. Soy consumption is not a risk factor for peanut sensitization. J Allergy Clin Immunol. 2008;121:1455-9. | Study design, Independent Variable
77 | Kramer, B.,Raczynska, J.,Kaczmarek, J.,Lukamowicz, J.,Pasowska, R.,Puchala, B.. Genetic and environmental conditions involved in assessment of the immunological state in children with atopic dermatitis. Rocz Akad Med Bialymst. 1995;40:439-47. | Study design, Independent Variable
78 | Kramer, M. S.,Chalmers, B.,Hodnett, E. D.,Sevkovskaya, Z.,Dzikovich, I.,Shapiro, S.,Collet, J. P.,Vanilovich, I.,Mezen, I.,Ducruet, T.,Shishko, G.,Zubovich, V.,Mknuik, D.,Gluchanina, E.,Dombrovskiy, V.,Ustinovitch, A.,Kot, T.,Bogdanovich, N.,Ovchinikova, L.,Helsing, E.. Promotion of Breastfeeding Intervention Trial (PROBIT): a randomized trial in the Republic of Belarus. Jama. 2001;285:413-20. | Independent Variable
79 | Kramer, M. S.,Moroz, B.. Do breast-feeding and delayed introduction of solid foods protect against subsequent atopic eczema?. J Pediatr. 1981;98:546-50. | Independent Variable
80 | Krogulska, A.,Wa̧ sowska-Królikowska, K.,Dynowski, J.. Usefulness of atopy patch tests with food allergens in diagnosis of food allergy in children with dermatitis atopica. Przeglad Pediatryczny. 2007;37:245-249. | Health Status, Independent Variable, Language
81 | Kucukosmanoglu, E.,Yazi, D.,Yesil, O.,Akkoc, T.,Gezer, M.,Bakirci, N.,Bahceciler, N. N.,Barlan, I. B.. Prevalence of egg sensitization in Turkish infants based on skin prick test. Allergol Immunopathol (Madr). 2008;36:141-4. | Study design
82 | Kummeling, I.,Thijs, C.,Huber, M.,van de Vijver, L. P.,Snijders, B. E.,Penders, J.,Stelma, F.,van Ree, R.,van den Brandt, P. A.,Dagnelie, P. C.. Consumption of organic foods and risk of atopic disease during the first 2 years of life in the Netherlands. Br J Nutr. 2008;99:598-605. | Study design
83 | Laubereau, B.,Brockow, I.,Zirngibl, A.,Koletzko, S.,Gruebl, A.,von Berg, A.,Filipiak-Pittroff, B.,Berdel, D.,Bauer, C. P.,Reinhardt, D.,Heinrich, J.,Wichmann, H. E.. Effect of breast-feeding on the development of atopic dermatitis during the first 3 years of life--results from the GINI-birth cohort study. J Pediatr. 2004;144:602-7. | Independent Variable
84 | Lee, J. M.,Neher, J. O.,Kelsberg, G.,Safranek, S.. Atopic Eczema and Early Introduction of Solid Foods. Am Fam Physician. 2015;92:523-4. | Study design
85 | Levin, M.,Goga, A.,Doherty, T.,Coovadia, H.,Sanders, D.,Green, R. J.,Kling, S.. Allergy and infant feeding guidelines in the context of resource-constrained settings. J Allergy Clin Immunol. 2016. | Study design
86 | Luoma, R.. Environmental allergens and morbidity in atopic and non-atopic families. Acta Paediatr Scand. 1984;73:448-53. | Independent Variable
87 | Majeed, R.,Rajar, U. D.,Shaikh, N.,Majeed, F.,Arain, A. A.. Risk factors associated with childhood asthma. J Coll Physicians Surg Pak. 2008;18:299-302. | Independent Variable
88 | Mauro-Martín, I. S.,Bodega-Villanueva, P.,Romero-Caamaño, E.,Micó-Moreno, V.,Garicano-Vilar, E.. Association between timing of food introduction in on first year old and the prevalence of allergies [spanish]. Revista Espanola de Nutricion Humana y Dietetica. 2014;18:145-154. | Language
89 | Mavale-Manuel, S.,Alexandre, F.,Duarte, N.,Albuquerque, O.,Scheinmann, P.,Poisson-Salomon, A. S.,de Blic, J.. Risk factors for asthma among children in Maputo (Mozambique). Allergy. 2004;59:388-93. | Independent Variable
90 | McKean, M.,Caughey, A. B.,Leong, R. E.,Wong, A.,Cabana, M. D.. The Timing of Infant Food Introduction in Families With a History of Atopy. Clin Pediatr (Phila). 2015;54:745-51. | Dependent Variable
91 | Metcalfe, J. R.,D’Vaz, N.,Makrides, M.,Gold, M. S.,Quinn, P.,West, C. E.,Loh, R.,Prescott, S. L.,Palmer, D. J.. Elevated IL-5 and IL-13 responses to egg proteins predate the introduction of egg in solid foods in infants with eczema. Clin Exp Allergy. 2016;46:308-16. | Health Status, Dependent Variable
92 | Midwinter, R. E.,Morris, A. F.,Colley, J. R.. Infant feeding and atopy. Arch Dis Child. 1987;62:965-7. | Study design, Independent Variable
93 | Mihrshahi, S.,Webb, K.,Almqvist, C.,Kemp, A. S.. Adherence to allergy prevention recommendations in children with a family history of asthma. Pediatr Allergy Immunol. 2008;19:355-62. | Dependent Variable
94 | Milner, J. D.,Stein, D. M.,McCarter, R.,Moon, R. Y.. Early infant multivitamin supplementation is associated with increased risk for food allergy and asthma. Pediatrics. 2004;114:27-32. | Independent Variable
95 | Miyake, Y.,Yura, A.,Iki, M.. Breastfeeding and the prevalence of symptoms of allergic disorders in Japanese adolescents. Clin Exp Allergy. 2003;33:312-6. | Study design
96 | Moore, W. J.,Midwinter, R. E.,Morris, A. F.,Colley, J. R.,Soothill, J. F.. Infant feeding and subsequent risk of atopic eczema. Arch Dis Child. 1985;60:722-6. | Independent Variable
97 | Morgan, J. B.,Lucas, A.,Fewtrell, M. S.. Does weaning influence growth and health up to 18 months?. Archives of Disease in Childhood: Education and Practice Edition. 2004;89:728-733. | Study design
98 | Morin, K. H.. Food Allergies: New Evidence for Peanut Introduction. MCN Am J Matern Child Nurs. 2016;41:188. | Study design
99 | Nakamura, Y.,Oki, I.,Tanihara, S.,Ojima, T.,Ito, Y.,Yamazaki, O.,Iwama, M.,Tabata, Y.,Katsuyama, K.,Sasai, Y.,Nakagawa, M.,Matsushita, A.,Hossaka, K.,Sato, J.,Hidaka, Y.,Uda, H.,Nakamata, K.,Yanagawa, H.. Relationship between breast milk feeding and atopic dermatitis in children. J Epidemiol. 2000;10:74-8. | Study design, Independent Variable
100 | | Language
101 | Natsume, O.,Kabashima, S.,Nakasato, J.,Yamamoto-Hanada, K.,Narita, M.,Kondo, M.. Early introduction of egg for infants with atopic dermatitis to prevent egg allergy: A double-blind placebo-controlled randomized clinical trial[abstract only]. Journal of Allergy and Clinical Immunology. 2016;137. | Study design
102 | Neild, V.. Diet and atopic eczema. Mod Midwife. 1994;4:22. | Study design
103 | Nwaru, B. I.,Erkkola, M.,Ahonen, S.,Kaila, M.,Haapala, A. M.,Kronberg-Kippila, C.,Salmelin, R.,Veijola, R.,Ilonen, J.,Simell, O.,Knip, M.,Virtanen, S. M.. Age at the introduction of solid foods during the first year and allergic sensitization at age 5 years. Pediatrics. 2010;125:50-9. | Dependent Variable
104 | Nwaru, B. I.,Takkinen, H. M.,Niemela, O.,Kaila, M.,Erkkola, M.,Ahonen, S.,Tuomi, H.,Haapala, A. M.,Kenward, M. G.,Pekkanen, J.,Lahesmaa, R.,Kere, J.,Simell, O.,Veijola, R.,Ilonen, J.,Hyoty, H.,Knip, M.,Virtanen, S. M.. Introduction of complementary foods in infancy and atopic sensitization at the age of 5 years: timing and food diversity in a Finnish birth cohort. Allergy. 2013;68:507-16. | Dependent Variable
105 | Oddy, W. H.,Sherriff, J. L.. Breastfeeding, body mass index, asthma and atopy in children. Asia Pac J Public Health. 2003. | Independent Variable
106 | Oddy, W. H.. Breastfeeding and asthma in children: findings from a West Australian study. Breastfeed Rev. 2000;8:5-11. | Independent Variable
107 | Oehling, A.. Importance of food allergy in childhood asthma. Allergol Immunopathol (Madr). 1981:71-3. | Study design
108 | Ogbuanu, I. U.,Karmaus, W.,Arshad, S. H.,Kurukulaaratchy, R. J.,Ewart, S.. Effect of breastfeeding duration on lung function at age 10 years: a prospective birth cohort study. Thorax. 2009;64:62-6. | Independent Variable
109 | Ozmert, E. N.,Kale-Cekinmez, E.,Yurdakok, K.,Sekerel, B. E.. Determinants of allergic signs and symptoms in 24-48-month-old Turkish children. Turk J Pediatr. 2009;51:103-9. | Study design
110 | Parihar, H.,Kumar, L.,Puri, R.,Kumar, V.. The incidence of allergic diseases and feeding patterns in children upto 2 years of age. Indian J Pediatr. 1984;51:7-12. | Study design
111 | Paton, J.,Kljakovic, M.,Ciszek, K.,Ding, P.. Infant Feeding Practices and Nut Allergy over Time in Australian School Entrant Children. Int J Pediatr. 2012;2012:675724. | Study design, Age
112 | Pesonen, M.,Kallio, M. J.,Ranki, A.,Siimes, M. A.. Prolonged exclusive breastfeeding is associated with increased atopic dermatitis: a prospective follow-up study of unselected healthy newborns from birth to age 20 years. Clin Exp Allergy. 2006;36:1011-8. | Independent Variable
113 | Peters, R. L.,Allen, K. J.,Dharmage, S. C.,Lodge, C. J.,Koplin, J. J.,Ponsonby, A. L.,Wake, M.,Lowe, A. J.,Tang, M. L.,Matheson, M. C.,Gurrin, L. C.. Differential factors associated with challenge-proven food allergy phenotypes in a population cohort of infants: a latent class analysis. Clin Exp Allergy. 2015;45:953-63. | Study design
114 | Peters, T. J.,Golding, J.. The epidemiology of childhood eczema: II. Statistical analyses to identify independent early predictors. Paediatr Perinat Epidemiol. 1987;1:80-94. | Independent Variable
115 | Pitt, Tj,Watson, W.,Ferguson, A.,Dimich-Ward, H.,Dybuncio, A.,Kozyrskyj, Al. Delay In The Introduction Of Allergenic Foods Is Not Associated With An Increased Risk For Sensitization In A High Risk Cohort [Abstract]. Journal of allergy and clinical immunology. 2010;125. | Study design
116 | Pohl, C. A.. Timing of cereal introduction to the infant diet. Patient Care for the Nurse Practitioner. 2006;9. | Study design
117 | Pohlabeln, H.. Effect modification by familial predisposition when analyzing the influence of breastfeeding and pet keeping on the development of allergic diseases in children [german]. Allergologie. 2012;35:44-53. | Language
118 | Poongadan, M. N.,Gupta, N.,Kumar, R.. Dietary pattern and asthma in India. Pneumonol Alergol Pol. 2016;84:160-7. | Age
119 | Poysa, L.,Pulkkinen, A.,Korppi, M.,Remes, K.,Juntunen-Backman, K.. Diet in infancy and bronchial hyperreactivity later in childhood. Pediatr Pulmonol. 1992;13:215-21. | Independent Variable
120 | Poysa, L.. Atopy in children with and without a family history of atopy. II. Skin reactivity. Acta Paediatr Scand. 1989;78:902-6. | Independent Variable
121 | Prasad, S.,Rana, R. K.,Sheth, R.,Mauskar, A. V.. A Hospital Based Study to Establish the Correlation between Recurrent Wheeze and Vitamin D Deficiency Among Children of Age Group Less than 3 Years in Indian Scenario. J Clin Diagn Res. 2016;10. | Independent Variable, Dependent Variable
122 | Pratt, H. F.. Breastfeeding and eczema. Early Hum Dev. 1984;9:283-90. | Independent Variable
123 | Pugh, R. J.. Infant feeding in perspective. Practitioner. 1982;226:1917-25. | Study design
124 | Quah, P. L.,Loo, E. X.,Lee, G. N.,Kuo, I. C.,Gerez, I.,Llanora, G. V.,Chan, Y. H.,Aw, M.,Shek, L. P.,Lee, B. W.. Clinical phenotype and allergen sensitization in the first 2 years as predictors of atopic disorders at age 5 years. World Allergy Organ J. 2015;8:33. | Independent Variable
125 | Rosenberg, K.. Early Introduction Reduces Risk of Some Food Allergies. Am J Nurs. 2017;117:65-66. | Study design
126 | Roslan, K.,Szczepanski, M.,Kaczmarski, M.,Zapolska, B.,Uscinowicz, M.,Wasilewska, J.,Solarz, E.. Environmental and constitutional conditions and food hypersensitivity in children. Rocz Akad Med Bialymst. 1995;40:448-51. | Study design, Health Status
127 | Satwani, H.,Rehman, A.,Ashraf, S.,Hassan, A.. Is serum total IgE levels a good predictor of allergies in children?. J Pak Med Assoc. 2009;59:698-702. | Study design
128 | Sausenthaler, S.,Heinrich, J.,Koletzko, S.. Early diet and the risk of allergy: What can we learn from the prospective birth cohort studies GINIplus and LISAplus?. American Journal of Clinical Nutrition. 2011;94. | Study design
129 | Sherriff, A.,Peters, T. J.,Henderson, J.,Strachan, D.. Risk factor associations with wheezing patterns in children followed longitudinally from birth to 3(1/2) years. Int J Epidemiol. 2001;30:1473-84. | Independent Variable
130 | Shohet, L.,Shahar, E.,Davidson, S.. Breast feeding as prophylaxis for atopic eczema: a controlled study of 368 cases. Acta Paediatr Hung. 1985;26:35-9. | Independent Variable
131 | Siltanen, M.,Kajosaari, M.,Poussa, T.,Saarinen, K. M.,Savilahti, E.. A dual long-term effect of breastfeeding on atopy in relation to heredity in children at 4 years of age. Allergy. 2003;58:524-30. | Independent Variable
132 | Silvers, K. M.,Frampton, C. M.,Wickens, K.,Pattemore, P. K.,Ingham, T.,Fishwick, D.,Crane, J.,Town, G. I.,Epton, M. J.. Breastfeeding protects against current asthma up to 6 years of age. J Pediatr. 2012;160. | Independent Variable
133 | Smith, P.. Dietary prevention of food allergies in infants. Australian Journal of Pharmacy. 2012;93:80-83. | Study design
134 | Sybilski, A. J.,Doboszyńska, A.,Samoliński, B.. Influence of selected risk factors on the development of allergy during the first year of life [polish]. Przeglad Pediatryczny. 2008;38:13-19. | Independent Variable, Language
135 | Ta, V.,Laubach, S.. Introduction of complementary foods and the relationship to food allergy. Pediatrics. 2014. | Study design
136 | Taitz, L.. Feeding children in the first year of life. Community Nurse. 1990;26:81-84. | Study design
137 | Takemura, Y.,Sakurai, Y.,Honjo, S.,Kusakari, A.,Hara, T.,Gibo, M.,Tokimatsu, A.,Kugai, N.. Relation between breastfeeding and the prevalence of asthma : the Tokorozawa Childhood Asthma and Pollinosis Study. Am J Epidemiol. 2001;154:115-9. | Independent Variable
138 | Tan, Jw- L.,Valerio, C.,Barnes, E. H.,Asperen, P. P.,Kakakios, A. M.,Campbell, D. E.. Early introduction of dietary egg reduces egg sensitization at 12 months of age in infants at risk of allergic disease [abstract only]. Journal of Allergy and Clinical Immunology. 2016;137. | Study design
139 | Taylor, B.. Infant feeding and allergy: fact and fiction. Midwife Health Visit Community Nurse. 1984;20:354-60. | Study design
140 | Tromp,, II,Briede, S.,Kiefte-de Jong, J. C.,Renders, C. M.,Jaddoe, V. W.,Franco, O. H.,Hofman, A.,Raat, H.,Moll, H. A.. Factors associated with the timing of introduction of complementary feeding: the Generation R Study. Eur J Clin Nutr. 2013;67:625-30. | Dependent Variable
141 | van Odijk, J.,Hulthen, L.,Ahlstedt, S.,Borres, M. P.. Introduction of food during the infant’s first year: a study with emphasis on introduction of gluten and of egg, fish and peanut in allergy-risk families. Acta Paediatr. 2004;93:464-70. | Study design, Dependent Variable
142 | Ventura, A.,De Seta, L.,Martelossi, S.,Florean, P.,Maggiore, G.,Salvatore, C. M.,Berzioli, M.,Guidobaldi, G.,Lorenzini, G.,Peressini, P.,Pesenti, P.,Rollo, G.,Sacher, B.,Santoro, L.,Stanzione, V.,Stranamore, D.,Zannerio, E.. Soy allergy and DSCG in atopic eczema: “much ado about nothing”?. Pediatr Med Chir. 1996;18:283-8. | Health Status, Independent Variable
143 | Verduci, E.,Banderali, G.,Peroni, D.,Lassandro, C.,Radaelli, G.. Duration of exclusive breastfeeding and wheezing in the first year of life: A longitudinal study. Allergol Immunopathol (Madr). 2016. | Independent Variable
144 | Visser, H. K.. Dietary influences on infection and allergy in infants: introduction. J Nutr. 2008;138. | Study design
145 | Waddell, L.. Introduction of solids in babies at risk of allergies. J Fam Health Care. 2014;24:22-7. | Study design
146 | Waidyatillake, N. T.,Simpson, J. A.,Allen, K. J.,Lodge, C. J.,Dharmage, S. C.,Abramson, M. J.,De Livera, A. M.,Matheson, M. C.,Erbas, B.,Hill, D. J.,Lowe, A. J.. The effect of breastfeeding on lung function at 12 and 18 years: A prospective cohort study. European Respiratory Journal. 2016;48:125-132. | Independent Variable
147 | Wegienka, G.,Ownby, D. R.,Havstad, S.,Williams, L. K.,Johnson, C. C.. Breastfeeding history and childhood allergic status in a prospective birth cohort. Ann Allergy Asthma Immunol. 2006;97:78-83. | Independent Variable
148 | West, C. E.,Hammarstrom, M. L.,Hernell, O.. Probiotics during weaning reduce the incidence of eczema. Pediatr Allergy Immunol. 2009;20:430-7. | Independent Variable
149 | White, J. M.,McFadden, J. P.. Contact allergens in food ingredients and additives: atopy and the hapten-atopy hypothesis. Contact Dermatitis. 2008;58:245-6. | Study design, Dependent Variable
150 | Woicka-Kolejwa, K.,Zaczeniuk, M.,Majak, P.,Pawlowska-Iwanicka, K.,Kopka, M.,Stelmach, W.,Jerzynska, J.,Stelmach, I.. Food allergy is associated with recurrent respiratory tract infections during childhood. Postepy Dermatol Alergol. 2016;33:109-13. | Study design, Dependent Variable
151 | Woś, H.,Cholewa, Z.,Brozek, G.. The influence of breast-feeding on the rate of occurrence of bronchial asthma in children at the younger school age. Pediatria Wspolczesna. 2003;5:21-27. | Independent Variable, Language
152 | Wright, A. L.,Holberg, C. J.,Martinez, F. D.,Halonen, M.,Morgan, W.,Taussig, L. M.. Epidemiology of physician-diagnosed allergic rhinitis in childhood. Pediatrics. 1994;94:895-901. | Dependent Variable
153 | Wright, A. L.,Holberg, C. J.,Taussig, L. M.,Martinez, F. D.. Factors influencing the relation of infant feeding to asthma and recurrent wheeze in childhood. Thorax. 2001;56:192-7. | Independent Variable
154 | Wright, A. L.,Holberg, C. J.,Taussig, L. M.,Martinez, F.. Maternal asthma status alters relation of infant feeding to asthma in childhood [not peer rev jl). Adv Exp Med Biol. 2000;478:131-7. | Study design
155 | Xu, M.,Wang, Y.,Dai, Z.,Zhang, Y.,Li, Y.,Wang, J.. Comparison of growth and nutritional status in infants receiving goat milk-based formula and cow milk-based formula: A randomized, double-blind study. Food and Nutrition Research. 2015;59. | Independent Variable, Dependent Variable
156 | Yamakawa, M.,Yorifuji, T.,Kato, T.,Yamauchi, Y.,Doi, H.. Breast-feeding and hospitalization for asthma in early childhood: a nationwide longitudinal survey in Japan. Public Health Nutr. 2015;18:1756-61. | Independent Variable
157 | Young, H. B.,Buckley, A. E.,Hamza, B.,Mandarano, C.. Milk and lactation: some social and developmental correlates among 1,000 infants. Pediatrics. 1982;69:169-75. | Study design, Independent Variable
158 | Zeiger, R. S.,Heller, S.,Mellon, M. H.,Forsythe, A. B.,O’Connor, R. D.,Hamburger, R. N.,Schatz, M.. Effect of combined maternal and infant food-allergen avoidance on development of atopy in early infancy: a randomized study. J Allergy Clin Immunol. 1989;84:72-89. | Independent Variable

4 Another systematic review examined the relationship between specific types and amounts of foods consumed during the complementary feeding period and risk of food allergies, atopic dermatitis/eczema, asthma, and allergic rhinitis. The timing of introduction of specific types of CFB (e.g., peanuts, eggs, fish) are addressed in that review.