# WHAT IS THE RELATIONSHIP BETWEEN THE TYPES AND AMOUNTS OF COMPLEMENTARY FOODS AND BEVERAGES CONSUMED AND GROWTH, SIZE, AND BODY COMPOSITION?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- What is the relationship between the types and amounts of complementary foods and beverages consumed and growth, size, and body composition?

### What is the answer to the question?

- Moderate evidence indicates that higher versus lower meat intake or meat versus iron-fortified cereal intake over a short duration (~3mo) during the complementary feeding period does not favorably or unfavorably influence growth, size, and/or body composition. There is insufficient evidence to determine a relationship between meat intake and prevalence/incidence of overweight or obesity.
- Limited evidence suggests that type or amount of cereal given does not favorably or unfavorably influence growth, size, body composition, and/or prevalence/incidence of overweight or obesity.
- Moderate evidence suggests that consumption of complementary foods with different fats and/or fatty acid composition does not favorably or unfavorably influence growth, size, or body composition. There is not enough evidence to determine a relationship between consumption of complementary foods with different fats and/or fatty acid composition and/or prevalence/incidence of overweight or obesity.
- Limited evidence suggests that sugar sweetened beverage consumption during the complementary feeding period is associated with increased risk of obesity in childhood, but is not associated with other measures of growth, size, and body composition.
- Limited evidence showed a positive association between juice intake and infant weight-for-length and child BMI z-scores.
- No conclusion could be made about the relationship between other complementary foods (vegetables, fruit, dairy products and/or cow’s milk, cereal-based products, milk-cereal drink, and/or categories such as “ready-made foods“) and growth, size, body composition, and/or prevalence/incidence of overweight or obesity.
- No conclusion could be made about the relationship between distinct dietary patterns during the complementary feeding period and growth, size, body composition, and/or prevalence/incidence of malnutrition, overweight or obesity.

### Why was this question asked?

- This important public question was identified as part of the U.S. Department of Agriculture and Department of Health and Human Services Pregnancy and Birth to 24 Months Project

### How was this question answered?

- A team of staff from the Nutrition Evidence Systematic Review conducted a systematic review in collaboration with a group of experts called a Technical Expert Collaborative.

### What is the population of interest?

- Generally healthy infants and toddlers who were fed complementary foods and beverages from ages 0-24 months and had growth, size, and/or body composition outcomes measured across the lifespan

### What evidence was found?

- Forty-nine articles were included that addressed type and/or amount of complementary foods and beverages consumed, including the introduction of specific complementary foods and beverages and dietary patterns during the complementary feeding period.
- The study designs included 18 randomized controlled trials, 1 non-randomized controlled trial, and 30 prospective cohort studies
- The studies varied in terms of the types and/or amounts of CFB examined, which included dietary patterns consumed during the complementary feeding period, meat, cereal, foods with different fatty acid composition, SSB, juice or 100% juice, and other CFB
- The gaps and limitations in the evidence may include the following:
  ○ Randomized controlled trials and studies that examine a wider range of specific types and amounts complementary foods and beverages,
  ○ Research that accounts for the rationale for type/amount of complementary foods and beverages given (e.g., reverse causality), and adjusts for potential confounders (e.g., human milk and/or formula-feeding and baseline growth status).

### How up-to-date is this review?

- This review includes literature from 01/1980 to 07/2016

## FULL REVIEW

### Systematic review question

What is the relationship between the types and amounts of complementary foods and beverages consumed and growth, size, and body composition?

### Conclusion statement

Moderate evidence indicates that higher versus lower meat intake or meat versus iron-fortified cereal intake over a short duration (~3mo) during the complementary feeding period does not favorably or unfavorably influence growth, size, and/or body composition. There is insufficient evidence to determine a relationship between meat intake and prevalence/incidence of overweight or obesity.

Limited evidence suggests that type or amount of cereal given does not favorably or unfavorably influence growth, size, body composition, and/or prevalence/incidence of overweight or obesity.

Moderate evidence suggests that consumption of complementary foods with different fats and/or fatty acid composition does not favorably or unfavorably influence growth, size, or body composition. There is not enough evidence to determine a relationship between consumption of complementary foods with different fats and/or fatty acid composition and/or prevalence/incidence of overweight or obesity.

Limited evidence suggests that sugar-sweetened beverage consumption during the complementary feeding period is associated with increased risk of obesity in childhood, but is not associated with other measures of growth, size, and body composition.

Limited evidence showed a positive association between juice intake and infant weight-for-length and child BMI z-scores.

No conclusion could be made about the relationship between other complementary foods (vegetables, fruit, dairy products and/or cow’s milk, cereal-based products, milk-cereal drink, and/or categories such as “ready-made foods“) and growth, size, body composition, and/or prevalence/incidence of overweight or obesity.

No conclusion could be made about the relationship between distinct dietary patterns during the complementary feeding period and growth, size, body composition, and/or prevalence/incidence of malnutrition, overweight or obesity.

### Grades

Moderate - Meat; Different Fats and/or Fatty Acid Composition; Limited - Juice; Sugar-Sweetened Beverages; Grade Not Assignable - Cereal; Other CFB; Dietary Patterns

### Summary

- This review includes 49 studies that examined the association between types and amounts of complementary foods and beverages (CFB) and growth, size, body composition, and/or overweight or obesity status including:
  ○ 18 randomized controlled trials (RCTs)
  ○ One non-RCT
  ○ 30 prospective cohort studies
- The types and amounts of CFB consumed during the complementary feeding (CF) period that were examined varied across studies. The types of CFB included meat, fortified and unfortified cereal, foods with different fats and/or fatty-acid composition, sugar-sweetened beverages (SSBs), juice drinks and/or 100% juice, and other CFB (e.g., fruits, vegetables, eggs, fish).
  ○ Distinct dietary patterns during the CF period were also examined but difficult to compare
  ○ Introduction of specific types of CFB was also examined but varied widely (e.g., SSB <6mo vs. never; ground meat/soy product <3, 4-6, >6mo)
- Growth, size, and body composition outcomes varied across studies. These outcomes included weight, length/height, body circumferences (e.g., head, arm, chest, waist), fat mass (FM), lean mass, weight-to-height ratio (e.g., body mass index (BMI), weight-for-length z-score (WLZ)), and/or incidence/frequency/prevalence/risk of malnutrition, overweight, or obesity measured either at a single time point or change over time.
- The relationship between the types and/or amounts of CFB and growth, size, and/or body composition remains unclear.
  ○ In many cases, the amount of CFB provided would not be expected to affect these outcomes over the limited duration of time in which it was tested or how long after the intervention subjects were followed-up
  ○ Given the normal variation in healthy child growth patterns, caution should be used when interpreting results between timing, types and amounts of CFB and outcomes for individuals based on findings at the population level.
- Additional factors that need to be considered when examining the relationship between types and/or amounts of CFB and growth, size, and/or body composition outcomes include:
  ○ Early infant milk feeding practices (human milk, formula, and/or mixed)
  ○ Variability of normal early infant growth patterns
  ○ Parental feeding styles and the rationale for choosing specific types of CFB (e.g., perceived infant readiness, infant growth or size, fear of inadequate milk supply, sleep promotion, responsive feeding, infant food neophobia/acceptance)
  ○ Cultural preference related to parental history and/or feeding practices

### Description of the evidence

This SR includes 49 studies that examined the association between the types and amounts of CFB and growth, size, and body composition. The study designs in this review included 18 RCTs (1–18), one of which was a cross-over design (1), one non-RCT (19), and 30 prospective cohort studies (20–49) (Supplemental Table S1). Multiple articles used the same cohorts but represented different outcomes, different exposures, or exposures/outcomes at different ages (41, 42, 40, 49, 51, 56, 32, 50, 31, 38, 39).

#### Description of subject characteristics

The studies included in this SR enrolled both girls and boys (~29-67% females) who were healthy, full-term infants According to the Human Development Index (50), 37 articles were from studies conducted in countries categorized as “very high”, and 12 articles were from studies conducted in countries categorized as “high. While most studies did not describe the race/ethnicity of subjects, they were all conducted in representative populations from the countries in which they were conducted.

A number of studies enrolled infants who were exclusively breastfed (EBF (4, 11–15, 17) or exclusively formula-fed (EFF (1, 9) up to at least 4 mo of age. The remaining studies varied in terms of whether infants were fed human milk, infant formula, or both and most adjusted for feeding method (e.g., BF duration) in analyses.

#### Description of types and amounts of complementary foods and beverages

The types of CFB commonly examined in these studies included meats, fortified and unfortified cereals/porridges, foods that varied in fats or fatty acid profiles, and sugar-sweetened beverages (SSBs), juice drinks, and 100% fruit juice. In most cases, cereal refers to infant cereals that were fortified with iron (Fe), and variably fortified with additional micronutrients (e.g., zinc). Fewer studies examined other foods and/or food groups such as fruit and/or vegetable snacks, biscuits, fried potatoes, confectionary or sweetened foods, home-based CFB (prepared with a blender according to a provided recipe), and self-made vs. ready-made CFB. Types and amounts of CFB were analyzed in several ways, such as different types of CFB, different amounts of the same CFB, by age of introduction of specific CFB, and dietary patterns during the CF period (Supplemental Table S1).

The included articles were categorized according to how types and/or amounts of CFB were assessed:

- Meat, with or without cereal (2, 3, 5, 11, 14, 15, 18, 32, 33, 39, 44, 49). These studies examined meat as a CFB, including meat intake compared to another CFB such as cereal, the amount of meat consumed, or meat introduction;
- Cereal (9, 11, 17, 35, 38, 49). These studies examined cereal(s), including different types of cereal, amount of cereal, or timing of cereal intake. Several articles randomized groups to receive meat vs. cereal, or meat and cereal vs. control. Those studies are not discussed in the “cereal” section to avoid redundancy with the “meat with or without cereal” section;
- CFB with different fats and/or fatty acid composition (4, 6, 10, 13). These studies examined different types of CFB including fish and egg that naturally contain or were manipulated to contain different amounts or types of fat;
- SSBs (26, 31–33, 38, 40, 43, 45). These studies examined either amount or timing of SSBs consumed during the CF period;
- Juice drinks and/or 100% juice (31–33, 38, 43, 45). These studies examined the consumption of juice, which may or may not have contained added sugar. Studies examined the amount or timing of juice, included 100% juice, juice drinks, and/or other beverages, during the CF period;
- Other CFB (8, 16, 19, 21, 22, 27, 29, 30, 32, 33, 36–38, 43, 44, 48, 49)(7, 8, 19, 21, 22, 27, 29, 30, 32, 33, 36–38, 43, 44, 49). These remaining studies examined other or multiple CFB, which were not addressed in the aforementioned categories (e.g., vegetables, ready-made foods, confectionary foods);
- Dietary patterns (12, 20, 23–25, 27, 28, 34, 41, 42, 46, 47). These studies examined dietary patterns during the CF period classified either by observation (e.g., macrobiotic diet) or statistical analyses (e.g., adherence scores for patterns derived from latent class, cluster, or principal component analysis).

#### Description of growth, size, and body composition outcomes

Outcomes that were reported in relation to types and amounts of CFB consumed included growth, size, and body composition at various ages, ranging from birth to 42 y (Supplemental Table S1). The majority of studies reported that standard procedures were used to obtain weight and height (e.g., measured from calibrated scales/stadiometers) and were assessed within the first two years of life (1, 3–9, 11, 12, 14, 15, 18, 19, 23, 24, 28, 36, 39, 48). However, a few studies obtained weight and/or length or height via maternal-report (31, 42, 47, 49), clinical records (2, 37), unstandardized or various methods (38, 44), or did not specifically report their methods (10, 13, 17, 20).

Nineteen studies determined BMI, BMI trajectory, BMIZ, and/or WLZ from measured (5, 9, 14, 15, 21, 25, 28, 29, 32–34, 38, 41, 43, 45) or reported (42, 44, 47, 49), weight and length. Eleven studies assessed adiposity according to fat mass (FM) and/or lean mass measured by skinfold thickness (3, 4, 22, 23, 28, 30, 36) (9),or whole-body dual-energy X-ray apsorptiometry (DXA) (41),(48),(29). Six studies assessed central adiposity, either waist circumference (WC) or abdominal fat (14, 26, 29, 33, 34, 44) measured using flexible tape (26, 33, 34), ultrasound (29), self-report (44), or non-specified methods (14). Fourteen studies reported head circumference (HC) (1, 4, 5, 7, 9–12, 15, 18, 24, 28, 36, 39) and six reported mid-upper arm circumference (MUAC) (1, 3, 7, 12, 28, 36).Seven studies assessed overweight or obesity (20, 26, 29, 40, 42, 44, 49), using standards according to BMI or WLZ. Two studies assessed malnutrition outcomes (e.g., wasting, stunting) (28, 46).

### Evidence synthesis

Results from the included studies are described according to specific CFB in Tables 1–6, placed after each respective section. Twenty-four of the 49 articles reported one or more significant associations, either positive, negative, or mixed, between types or amounts of CFB and growth, size, body composition, and/or risk of malnutrition, overweight or obesity (5, 14, 15, 19, 21, 23, 27, 28, 30–34, 37–42, 44–47, 49). Twenty-five of the 49 articles found no relationship between types and amounts of CFB and growth, size, body composition, and/or risk of overweight or obesity (1–4, 6–13, 16–18, 20, 22, 24–26, 29, 35, 36, 43, 48).

#### Meat

Twelve articles, including seven RCTs (2, 3, 5, 11, 14, 15, 18) and five articles from four observational studies (32, 33, 39, 44, 49) examined the relationship between meat intake and growth, size, body composition, and/or risk of overweight or obesity outcomes. Studies varied in terms of whether they assessed meat compared to cereal, meat and cereal compared to controls, or the amount of meat consumed (see Table 1).

Krebs et al. (5) reported that BF infants consuming meat compared to Fe-fortified cereal from 5-7 mo had a significantly greater rate of HC growth from 7-12 mo, but no significant differences in HC growth 4-7 mo, weight-for-length 4-7 mo or 7-12 mo, weight growth rate at 4-7 mo or 7-12 mo, WAZ 4-12 mo, length growth rate 4-7 mo or 7-12 mo, or LAZ 4-12 mo. Tang et al. (15) reported that Chinese infants randomly assigned to the meat vs. cereal groups had a smaller decline in WAZ, smaller decline in LAZ and greater increase in length from 6-18 mo but no significant differences in WLZ or in HC, or HC z-score from 6-18 mo. Tang and Krebs (14) also reported that U.S. infants randomly assigned to meat vs. cereal groups had significantly greater mean change in WAZ and LAZ from 5-9 mo, but there were no differences between groups in WLZ or BMIZ from 5-9 mo or in WC at 9 mo of age. In two other RCTs, there were no significant group differences in weight, length, or HC in the first year of life between those who received meat and Fe-fortified cereal relative to control groups (11, 18).

Two RCTs found no relationship between amount of meat consumed and growth, size, or body composition outcomes prior to 10 mo of age (2, 3). Three articles from two observational studies also examined meat intake (32, 33, 39). Garden et al. (33) and Garden et al. (32) reported significant positive associations between meat intake at 18 mo and BMI trajectory (i.e., ‘early and persistent’, ‘late increase’, or ‘normal’ according to CDC percentile curves) at different ages, 8 y and birth-11.5 y (in boys only). Morgan et al. (39) found that meat intake from 4-12 mo was significantly associated with higher weight gain from 4-12 mo but this did not persist in the fully-adjusted models or at older age intervals (4-16 mo, 4-24 mo), and there was no association with length or HC outcomes.

Meat introduction. Two observational studies examined the introduction of meat (44, 49). Zheng et al. (49) reported no significant association between age of ground meat/soy introduction and overweight or obesity or BMI at age 4-5 y. Schack-Nielsen et al. (44) found that, among other relationships identified, later introduction of meat was associated with decreased BMI and risk of overweight at 42 y, but not at 20-34 y of age.

Table 1 Studies that examined meat, with or without cereal, and growth, size, and body composition

Reference^1^, country, analytic N | Independent variable/exposure^2^ | Results for weight status | Results for body composition | Results for weight | Results for length/height | Results for head circumference
Dube et al., 2010 (2) RCT; Germany; N: 97 | Low meat group: meals 8% meat by weight for 7mo, ages 4-11mo vs. High meat group: meals 12% meat by weight for 7mo, ages 4-11mo | | | Weight at 4, 7, or 10mo, NSGD
Engelmann et al., 1998 (3); RCT; Denmark; N: 41 | Low meat group: puree with 10g/d of meat for 2mo, ages 8-10mo vs. High meat group: puree with 27g/d of meat for 2mo, ages 8-10mo | | Change in MUAC or triceps skinfold thickness at 10mo, NSGD | Change in weight at 10mo, NSGD | Change in crown-heel length at 10mo, NSGD
Garden et al., 2011 (33); Australia; N: 362 (339 WC) | Meat intake (g, % energy) at 18mo; e.g., chicken nuggets, ground beef, beef sausages, ham | | BMI at 8y: g, β=0.25; 95% CI:0.04, 0.45, P=0.02; % energy, β=0.27; 95% CI:0.07, 0.47, P=0.01; WC at 8y: g, β=0.59; 95% CI:0.03, 1.15, P=0.04; % energy, β=0.63; 95% CI:0.10, 1.17, P=0.02
Garden et al., 2012 (32); Australia; N: 298 | In boys, meat intake (g, % energy) at 18mo; e.g., chicken nuggets, ground beef, beef sausages, ham | | Early and Persistent vs. Normal or Late Increase BMI from 0-11.5y: g, median 38.8 vs. 18.6 vs. 24.1, P=0.01; % energy, 9.2 vs. 4.4 or 4.1, P=0.01
Garden et al., 2012 (32); Australia; N: 298 | In girls, meat intake (g, % energy) at 18mo; e.g., chicken nuggets, ground beef, beef sausages, ham | | Any BMI from 0-11.5y, NSA
Krebs et al., 2006 (5); RCT; U.S.; N: 72 | Meat group: pureed beef for 2mo, ages 5-7mo; Cereal group: Fe-fortified infant cereal for 2mo, ages 5-7mo (1:2 ratio of cereal to human milk/water) | | Mean weight-for-length percentiles at either 4-7mo or 7-12mo intervals, NSGD | Weight growth rate from 4-7mo, or from 7-12mo , or WAZ from 4-12mo , NSGD | Length growth rate from 4-7mo, or from 7-12mo , or LAZ from 4-12mo, NSGD | HC growth from 7-12mo: 0.48, SE: 0.018 vs. 0.41, SE: 0.019, P=0.02; from 4-7mo, NSGD
Makrides et al., 1998 (11); RCT; Australia; N: 62 (Intervention, 36; Control, 26) | Meat+cereal group: 4, 30-40g servings/wk of red meat and 4, 113g jars/wk of Fe-fortified cereal for 2mo, ages 4-6mo; Control group: Standard nutritional advice to consume Fe-fortified infant cereal for 2mo, ages 4-6mo | | | Weight at 9 or 12mo, NSGD | Length at 9 or 12mo, NSGD | HC at 9 or 12mo, NSGD
Morgan et al., 2004 (39); U.K.; N: 144 | Meat intake: red (beef, pork and lamb) and white (chicken, turkey, fish) meat from age 4-12mo | | | Weight gain 4-12mo: β=0.40, 95%CI: 0.005, 0.79, P=0.05; effect disappeared after adjusting for protein intake, NSA | Length 4-12mo, NSA | HC 4-12mo, NSA
Morgan et al., 2004 (39); U.K.; N: 144 | Meat intake: red (beef, pork and lamb) and white (chicken, turkey, fish) meat from age 4-16mo | | | Weight 4-16mo, NSA | Length 4-16mo, NSA | HC 4-16mo, NSA
Morgan et al., 2004 (39); U.K.; N: 144 | Meat intake: red (beef, pork and lamb) and white (chicken, turkey, fish) meat from age 4-24mo | | | Weight 4-24mo , NSA | Length 4-24mo, NSA | HC 4-24mo, NSA
Schack-Nielsen et al., 2010 (44); Denmark; N: 5068 | Meat introduction continuous, mo | At 42y, Overweight OR 0.93, 95%CI: 0.87, 1.00, P=0.044; Obesity, NSA | BMIZ at ages: 42y β=−0.032, 95%CI: −0.059, −0.005; 20-34y, NSA
Schack-Nielsen et al., 2010 (44); Denmark; N: 5068 | Meat introduction ≥4 vs. <4mo | Overweight at 42y, NSA
Tang et al., 2014 (15); RCT; China; N: 1318 | Meat group: boiled pork for 12mo, ages 6-18mo vs. Cereal group: commercial rice cereal product for 12mo, ages 6-18mo | | Change in WLZ from 6-18mo, NSGD | Mean change in WAZ from 6-18mo: −0.35, SD: 0.60 vs. −0.43, SD: 0.61, P=0.05. Change in weight from 6-18mo, NSGD | Mean change in LAZ from 6-18mo: −0.43, SD: 0.72 vs. −0.54, SD: 0.67, P<0.01. Length from 6-18mo, 13.01cm, SD: 1.9 vs. 12.75cm, SD: 1.8, P=0.01 | Change in HC or HCZ from 6-18mo, NSGD
Tang and Krebs, 2014 (14); RCT; U.S.; N: 42 | Meat group: pureed meat and gravy for 4mo, ages ~5-9mo vs. Cereal group: Fe or FeZn-fortified infant cereal for 4mo, ages ~5-9mo; asked to avoid meats | | WLZ or BMIZ from 5 to 9mo, NSGD; WC at 9mo, NSGD | Mean change in WAZ 5-9mo: 0.24, SD: 0.19 vs. −0.07, SD: 0.17, P<0.05 | Mean change in LAZ 5-9mo: 0.14, SD: 0.12 vs. −0.27, SD: 0.24, P<0.05
Yeung and Zlotkin, 2000 (18); RCT; Canada; N: 103 (Intervention, 49; Control, 54) | Meat+cereal group: pureed meat and Fe-fortified infant cereals for 6mo, ages 6 −12mo; all other foods allowed at parents’ discretion except vitamin/mineral supplements containing Fe and Fe-fortified formulas vs. Control group: no dietary intervention | | | Weight at 8, 10, or 12mo, NSGD | Length at 8, 10, or 12mo, NSGD | HC at 8, 10, or 12mo, NSGD
Zheng et al., 2015 (49); China; N: 40,510 | Meat/soy introduction: ≤3, 4-6, >6mo | Overweight or obesity at 4-5y, NSA | BMI at 4-5y, NSA

1 All studies followed a prospective cohort design unless noted as RCT or non-RCT

2 The independent variable/exposure of interest included types and/or amounts of CFB, which encompassed dietary patterns during the complementary feeding period and timing of specific CFB; this section of studies examined meat with or without cereal.

3 Outcomes were organized for practicality into columns: weight status, body composition, weight, length or height, and head circumference. Results described in the respective columns are based on outcome similarity and in accordance with the analytical framework as follows: Weight status included risk/incidence/prevalence/frequency of malnutrition, healthy weight, overweight, or obesity; Body composition included measures, indices, and proxies of overall adiposity such as lean mass, fat mass (FM), % body fat, weight-to-height ratios such as BMI, BMIZ, WLZ, central adiposity or waist circumference, and arm or thigh circumferences; Weight included weight-specific measures such as weight-for-age z-score (WAZ), Length or Height included length-specific measures such as length-for-age z-score (LAZ); Head circumference included head circumference

Abbreviations: BF, breast-fed; BMIZ, BMI z-score; CFB, complementary food/beverage; Fe, iron; FF, formula-fed; HC, head circumference; HCZ, head circumference z-score; LAZ, length for age z-score; MUAC, mid-upper arm circumference; NR, not reported; NSA, no significant association; NSGD, no significant group differences; RCT, randomized controlled trial; WAZ, weight for age z-score; WC, waist circumference; WLZ, weight for length z-score; Zn, zinc

#### Cereal

The studies that examined cereal and meat intake or compared cereal intake relative to meat intake are discussed in the previous section. Three articles from RCTs examined cereal as a CFB in relation to multiple outcomes, including body composition, weight, length, and HC prior to 18mo of age (1, 9, 17) (see Table 2). Davidsson et al. (1) reported no differences in a cross-over trial with EFF infants receiving specially-developed weaning cereals that were fortified to match commercially-available fortified cereals made with wheat/soy or wheat/milk for 4 wk each and weight, length, HC, or arm or chest circumference at 7-17 wk. Lonnderdal and Chen (9) reported no differences between EFF infants receiving 25g/d of cereal (fortification not specified) vs. no cereal from age 4-7 mo and weight-for-height, skinfold thickness, weight gain, length gain, or HC from 4-7 mo of age. Walter et al. (17) reported no differences between EBF infants, who were randomized at 4 mo to receive 30 g/d of Fe-fortified vs. non-fortified cereal, in weight or length at 8, 12, or 15 mo of age.

Three articles from observational studies (35, 38, 49) also examined the relationship between cereal as a CFB and growth, size, body composition, and/or risk of overweight or obesity outcomes (see Table 3). Hertrampf et al. (35) reported no significant differences between infants consuming Fe-fortified cereal compared to routine CFB (including cereal that was not specified as fortified) from ~3-6 mo and weight at 8 or 12 mo of age. Using data from the PROBIT trial, Kramer et al. (38) found that any intake of cereal (non-fortified adult’ cereals) vs. none at 3 mo of age was associated with lower WAZ, LAZ and HC from 3-6 mo of age, but not with WLZ at any time point (38). Kramer et al. (38) reported no significant associations between cereal intake and outcomes at either 6-9 mo or 9-12 mo of age. Finally, Zheng et al. (49) found no significant associations between introduction to rice cereal/porridge and risk of either overweight or obesity at age 4-5 y.

Table 2 Studies that examined cereal, and growth, size, and body composition

Reference^1^, country, analytic N | Independent variable/exposure^2^ | Results for weight status | Results for body composition | Results for weight | Results for length/height | Results for head circumference
Davidsson et al., 1996 (1); RCT; Scotland; N: 57 | FF infants received each cereal ad lib for 4wk each at ages 7-17wk: wheat/soy: 1.8-8% fiber vs. wheat/milk: 2-5.3% fiber | | Arm or chest circumference at 7-17wk, NSA | Weight at 7-17wk, NSA | Length at 7-17wk, NSA | HC at 7-17wk, NSA
Hertrampf et al., 1990 (Hertrampf, 1990); Chile; N: 189 4mo; 187 12mo | Fe-fortified cereal: received 20g/d at 4mo and 40g/d at 6mo vs. Control: routine CFB | | | Weight-for-age adequacy at 8, or 12mo, NSA
Kramer et al., 2004 (38); Belarus; N: 17,046 | Cereal intake (any vs. none) at ages 3, 6, or 9mo | | WLZ 3-6, NSA | WAZ 3-6mo, β=−0.293, 95% CI: −0.386, −0.199, P=NR | LAZ 3-6mo, β=−0.240, 95% CI: −0.353, −0.127, P=NR | HC 3-6mo , β=−0.291, 95% CI: −0.463, −0.120, P=NR
Lonnerdal and Chen., 1990 (9); RCT; China; N: NR | EFF infants vs. FF+cereal for 3mo, ages 4-7mo | | Weight-for-length from 4-7mo, NSGD; Skinfold thickness, data NR, NSGD | Weight gain from 4-7mo, NSGD | Length gain from 4-7mo, NSGD | HC from 4-7mo, data NR, NSGD
Walter et al., 1993 (17); RCT; Chile; N: 444 8mo; 370 12mo; 340 15mo | Fe-fortified cereal + breastmilk vs. Unfortified cereal + breastmilk, age 4-15mo | | | Weight at 8, 12, or 15mo, NSGD | Length at 8, 12, or 15mo, NSGD
Zheng et al., 2015 (49); China; N: 40,510 | Rice cereal/porridge introduction: ≤3, 4-6, >6mo | Overweight or obesity at 4-5y, NSA | BMI at 4-5y, NSA

1 All studies followed a prospective cohort design unless noted as randomized controlled trial (RCT) or non-RCT.

2 The independent variable/exposure of interest included types and/or amounts of CFB, which encompassed dietary patterns during the complementary feeding period and timing of specific CFB; this section of studies examined cereal.

3 Outcomes were organized for practicality into columns: weight status, body composition, weight, length or height, and head circumference. Results described in the respective columns are based on outcome similarity and in accordance with the analytical framework as follows: Weight status included risk/incidence/prevalence/frequency of malnutrition, healthy weight, overweight, or obesity; Body composition included measures, indices, and proxies of overall adiposity such as lean mass, fat mass (FM), % body fat, weight-to-height ratios such as BMI, BMIZ, WLZ, central adiposity or waist circumference, and arm or thigh circumferences; Weight included weight-specific measures such as weight-for-age z-score (WAZ), Length or Height included length-specific measures such as length-for-age z-score (LAZ); Head circumference included head circumference

Abbreviations: BF, breast-fed; CFB, complementary food/beverage; EFF, exclusively formula-fed; Fe, iron; FF, formula-fed; HC, head circumference; LAZ, length for age z-score; NR, not reported; NSA, no significant association; NSGD, no significant group differences; RCT, randomized controlled trial; WAZ, weight for age z-score; WLZ, weight for length z-score

#### CFB with different fat/fatty acid composition

Table 3 describes results from 4 RCTs, which examined the influence of CFB that varied in fatty acid profiles (4, 6, 10, 13). No relationship was found between groups consuming CFB that differed in fatty acid content with respect to growth, size, or body composition outcomes. Hoffman et al. (4) found no significant differences between infants randomly assigned to receive one jar/d of CFB with or without egg-yolk for 6 mo (ages 6-12 mo) in weight, length, skinfold thickness, or HC at 6, 9, or 12 mo of age. Libuda et al. (6) randomly assigned infants to receive rapeseed oil, salmon, or corn-oil from 4-10 mo, but found no differences between groups in weight or length at 10 mo of age. Makrides et al. (10) randomly assigned infants (BF and/or FF) to consume eggs (~ 4/wk, regular or omega-3 enriched) or receive no dietary intervention for 6 mo, and reported no differences in weight, length, or HC at 12 mo of age. Schwartz et al. (13) found no significant differences between infants randomly assigned to receive one jar/d of CFB with either rapeseed oil vs. corn oil with respect to weight at 10 mo or weight gain from 4 to 10 mo of age.

Table 3 Studies that examined CFB with different fats/fatty acid composition and growth, size, and body composition

Reference^1^, country, analytic N | Independent variable/exposure^2^ | Results for weight status | Results for body composition | Results for weight | Results for length/height | Results for circumference
Hoffman et al., 2004 (Hoffman, 2004); RCT; U.S.; N: 51 | DHA-enriched group: CFB enriched with DHA from egg-yolk, ages 6-12mo vs. Control: unenriched CFB, ages 6-12mo | | Skinfold thickness at 6, 9, or 12mo, NSGD | Weight at 6, 9, or 12mo, NSGD | Length at 6, 9, or 12mo, NSGD | HC at 6, 9, or 12mo, NSGD
Libuda et al., 2015 (6); RCT; Germany; N: 155-158 | Rapeseed oil (ALA) group: CFB with rapeseed oil, ages 4-10mo vs. Fish group: Salmon 2x/wk (preformed DHA), ages 4-10mo vs. Corn oil (LA) group: CFB with corn oil, ages 4-10mo | | | Weight at 10mo, NSGD | Length at 10mo, NSGD
Makrides et al., 2002 (10); RCT; Australia; N: 137 | Regular egg group: 4 eggs/wk for 6mo, ages 6-12mo; vs. n-3 egg group: 4 DHA-enriched eggs/wk for 6mo, ages 6-12mo; vs. Control group: Standard weaning diet of choice for 6mo, ages 6- 12mo | | | Weight at 12mo, NSGD | Length at 12mo, NSGD | HC at 12mo, NSGD
Schwartz et al., 2009 (13); RCT; Germany; N: 102 | Rapeseed oil group: meat-based CFB with LA/ALA ratio of 3.9 for 6mo, ages 4-10mo; vs. Corn oil group (control): meat-based CFB with LA/ALA ratio of 35.7 for 6mo, ages 4-10mo | | | Weight at 10mo or gain from 4-10mo, NSGD

1 All studies, except those noted as RCT or non-RCT, followed a prospective cohort design

2 The independent variable/exposure of interest included types and/or amounts of CFB, which encompassed dietary patterns during the complementary feeding period and timing of specific CFB; this section of studies examined CFB with either different fats or fatty acid composition.

3 Outcomes were organized for practicality into columns: weight status, body composition, weight, length or height, and head circumference. Results described in the respective columns are based on outcome similarity and in accordance with the analytical framework as follows: Weight status included risk/incidence/prevalence/frequency of malnutrition, healthy weight, overweight, or obesity; Body composition included measures, indices, and proxies of overall adiposity such as lean mass, fat mass (FM), % body fat, weight-to-height ratios such as BMI, BMIZ, WLZ, central adiposity or waist circumference, and arm or thigh circumferences; Weight included weight-specific measures such as weight-for-age z-score (WAZ), Length or Height included length-specific measures such as length-for-age z-score (LAZ); Head circumference included head circumference

Abbreviations: ALA, alpha-linolenic acid; BF, breast-fed; CFB, complementary food/beverage; DHA, docosahexaenoic acid; FF, formula-fed; HC, head circumference; LA, linoleic acid; NR, not reported; NSA, no significant association; NSGD, no significant group differences; RCT, randomized controlled trial

#### SSBs

Five articles examined SSB intake (26, 32, 33, 40, 43) (see Table 4).One article reported that any vs. no intake of SSBs, including during infancy was associated with higher prevalence of obesity at age 6 y and that higher frequency of SSB intake (≥3/wk vs. never) at age 10-12 mo was associated with a 2-fold increase in odds of obesity at age 6 y (40). In addition, SSB introduction before age 6 mo vs. never during infancy was associated with 92% higher odds of obesity at age 6 y. Four articles reported no association with BMI, BMIZ, odds of obesity or abdominal obesity (26, 32, 33, 43). Specifically, there were no significant associations between intake of SSBs (which included cordials, fruit drinks, and soft drinks but excluded juice) at 18mo and BMI-trajectory at 8 y (33) or from birth-11.5 y (32). Cantoral et al. (26) reported no significant association between SSB introduction (based on the sum of daily intake of soda, commercial fruit drinks, or flavored water with sugar exclusive of natural fruit juice) at or before 12 mo vs. after 12 mo of age and odds of obesity or abdominal obesity at age 8-14 y. Santorelli et al. (43) found no significant association between introduction of SSBs, including cola, lemonade, sweetened tea and pre-prepared ‘baby’ drinks, before 17 wk and BMIZ at 3 y of age.

#### Juice drinks and 100% fruit juice

Six articles examined juice consumption primarily at or <1y of age (31–33, 38, 43, 45) (see Table 4). Juice was inconsistently described and juice consumption was defined differently across studies as follows: any vs. no intake of ‘juice or other liquids’ at ages 1, 3, 6, or 9 mo of age (38); fluid oz/d of orange juice or 100% fruit juice at 0, 1-7, 8-15,or >16 oz/d (45); servings of “juice” at 0, 1, or >1 serving/2d (31); and intake of “non-milk beverages” including juice,cordials, fruit drinks, and soft drinks (32, 33). Two studies found significant positive associations between juice consumption and weight relative to length (38, 45) but both studies reported additional null results. Results from Kramer et al. show that intake of juice at 9 mo was associated with higher WLZ from 9-12 mo of age but not WAZ, LAZ, or HC at any age (38). Sonneville et al. (45) found that 8-15 oz/d of fruit juice at 1 y vs. none was associated with increased BMIZ at 7.7 y, but lesser or greater amounts (1-7 oz, or >16 oz/d) were not associated with BMIZ at 7.7 y. In addition, the amount of fruit juice at 1 y was not associated with BMIZ at 3.1 y in fully-adjusted models. Gaffney et al. (31) found that infants who were given greater amounts of juice (>1 serving of juice/2d vs. none) had significantly higher WAZ at 12 mo. However, there were no significant associations between lesser amounts (≤1 serving of juice/2d vs. none) and WAZ at 12 mo. Garden et al. (33) and Garden et al. (32) found no association between intake of non-milk beverages which included juice, cordials, fruit drinks, and soft drinks at 18 mo and BMI-trajectory at 8y (33) or from birth-11.5 y (32). Collectively, the findings from these observational studies suggest positive associations but are inconsistent given the variation in the definitions and amounts of juice intake and outcomes at different ages.

Table 4 Studies that examined SSB, juice drinks and/or 100% juice and growth, size, and body composition

Reference^1^, country, analytic N | Independent variable/exposure^2^ | Results for weight status | Results for body composition | Results for weight | Results for length/height | Results for head circumference
Cantoral et al., 2016 (26); Mexico; N: 227 | SSB introduction, ≤12 vs >12mo: sum daily intake of soda, commercial fruit drinks, flavored water with sugar; excludes natural fruit/vegetable juice | Obesity at 8-14y, NSA | Abdominal obesity at 8-14y, NSA
Garden et al., 2011 (33); Australia; N: 362; 339 for WC | SSB intake (g, % energy) at age 18mo; sweetened drinks including cordials, fruit drinks, and soft drinks | | BMI at 8y, NSA; WC at 8y, NSA
Garden et al., 2011 (33); Australia; N: 362; 339 for WC | Juice+SSB intake (g, % energy) at age 18mo; non-milk beverages including juice, cordials, fruit drinks, and soft drinks | | BMI at 8y, NSA; WC at 8y, NSA
Garden et al., 2012 (32); Australia; N: 298 | In boys, SSB intake (g, % energy) at age 18mo; sweetened drinks including cordials, fruit drinks, and soft drinks | | BMI trajectory birth-11.5y, NSA
Garden et al., 2012 (32); Australia; N: 298 | In girls, SSB intake (g, % energy) at age 18mo; sweetened drinks including cordials, fruit drinks, and soft drinks | | BMI trajectory birth-11.5y, NSA
Garden et al., 2012 (32); Australia; N: 298 | In boys, Juice+SSB intake (g, % energy) at age 18mo; non-milk beverages including juice, cordials, fruit drinks, and soft drinks | | BMI trajectory birth-11.5y, NSA
Garden et al., 2012 (32); Australia; N: 298 | In girls, Juice+SSB intake (g, % energy) at age 18mo; non-milk beverages including juice, cordials, fruit drinks, and soft drinks | | BMI trajectory birth-11.5y, NSA
Pan et al., 2014 (40); U.S.; N: 1189 | SSB introduction: <6mo vs. never; SSB included juice drinks, soft drinks, soda, sweet tea, and Kool-Aid | Obesity at 6y: OR 1.92, 95% CI: 1.01, 3.66, P<0.05
Pan et al., 2014 (40); U.S.; N: 1189 | SSB introduction: <6 vs. ≥6mo; | Obesity at 6y, NSA
Pan et al., 2014 (40); U.S.; N: 1189 | SSB introduction: never vs. ≥ 6mo; | Obesity at 6y, NSA
Pan et al., 2014 (40); U.S.; N: 1189 | SSB intake: any vs. none during infancy | Obesity at 6y: prevalence 17% vs. 8.6%; OR: 1.63, 95%CI: 1.03, 2.56, P <0.05
Pan et al., 2014 (40); U.S.; N: 1189 | SSB frequency: ≥3/wk vs. never during age 10-12mo | Obesity at 6y: OR 2, 95%CI: 1.02, 3.90, P<0.05
Pan et al., 2014 (40); U.S.; N: 1189 | SSB frequency: ≥3/wk vs. <1/wk < during age 10-12mo | Obesity at 6y, NSA
Pan et al., 2014 (40); U.S.; N: 1189 | SSB frequency: ≥3/wk vs. 1-<3/wk during age 10-12mo | Obesity at 6y, NSA
Santorelli et al., 2014 (43); U.K.; N: 1327 | SSB introduction: <17wk or not; cola, lemonade, sweetened tea and pre-prepared ‘baby’ drinks | | BMIZ at 3y, NSA
Gaffney et al., 2012 (31); U.S.; N: 691 | Juice intake intensity in the first year: >1 vs. 0 serving/2d; type of juice NR | | | WAZ at 12mo, β=0.25, P=0.002
Gaffney et al., 2012 (31); U.S.; N: 691 | Juice intake intensity in the first year: ≤1 vs. 0 serving/2d; type of juice NR | | | WAZ at 12mo, NSA
Kramer et al., 2004 (38); Belarus; N: 17,046 | Juice/other liquids, any vs. none at 1, 3, 6, or 9mo | | WLZ from age 9-12mo: β=0.061, 95% CI: 0.003, 0.119, P=NR; from 1-3, 3-6, and 6-9mo, NSA | WAZ from age 1-3, 3-6, 6-9 or 9-12mo, NSA | LAZ from age 1-3, 3-6, 6-9 or 9-12mo, NSA | HC from age 1-3, 3-6, 6-9 or 9-12mo, NSA
Sonneville et al., 2015 (45); U.S.; N: 1163 | Fruit juice (orange juice or 100% fruit juice) intake at age 1y: 0, 1-7, 8-15, 16-31, or >32oz | | BMIZ at 7.7y: 1-7oz: β=0.07, 95%CI: −0.06, 0.21; 8-15oz: β=0.23, 95%CI: 0.005, 0.40; >16oz: β=0.27, 95%CI: −0.05, 0.59 vs. 0oz, P=0.05; BMIZ at 3.1y, NSA

1 All studies, except those noted as RCT or non-RCT, followed a prospective cohort design

2 The independent variable/exposure of interest included types and/or amounts of CFB, which encompassed dietary patterns during the complementary feeding period and timing of specific CFB; this section of studies examined sugar-sweetened beverage, juice drinks, and/or 100% juice.

3 Outcomes were organized for practicality into columns: weight status, body composition, weight, length or height, and head circumference. Results described in the respective columns are based on outcome similarity and in accordance with the analytical framework as follows: Weight status included risk/incidence/prevalence/frequency of malnutrition, healthy weight, overweight, or obesity; Body composition included measures, indices, and proxies of overall adiposity such as lean mass, fat mass (FM), % body fat, weight-to-height ratios such as BMI, BMIZ, WLZ, central adiposity or waist circumference, and arm or thigh circumferences; Weight included weight-specific measures such as weight-for-age z-score (WAZ), Length or Height included length-specific measures such as length-for-age z-score (LAZ); Head circumference included head circumference

Abbreviations: BF, breast-fed; BMIZ, BMI z-score; CFB, complementary food/beverage; HC, head circumference; LAZ, length for age z-score; NR, not reported; NSA, no significant association; NSGD, no significant group differences; RCT, randomized controlled trial; SSB, sugar-sweetened beverage; WAZ, weight for age z-score; WLZ, weight for length z-score

#### Other CFB

Sixteen articles examined distinct types, amounts, groups, or introductions of other CFB (7, 8, 19, 21, 22, 27, 29, 30, 32, 33, 36–38, 43, 44, 49) using different assessment methods and are described in more detail in Table 5. These other CFB were examined during intervals or at specific ages, primarily between 4 and 12 mo, relative to various outcomes ranging in age from 4 mo up to 42 y. Although a few significant associations were identified (see Table 5), there was insufficient evidence, inconsistency, and substantial methodological limitations across these studies that prevented conclusions from being drawn.

Types of Other CFB. Lind et al. (7) reported no differences between groups randomized to receive regular-phytate vs. reduced-phytate milk-cereal drink and porridge from 6-12 mo in WAZ, LAZ, MUAC, or HC at 6, 12, or 18 mo of age (7). Liu et al. (8) found no differences between BF infants and toddlers receiving a fortified (Fe, Zn, vitamin A, calcium, folic acid) or non-fortified biscuit daily for 3 mo in weight or length at ages 9-16 mo of age. de Silva et al. (19) reported that infants who were assigned to receive ‘home-based CFB’ (i.e., a CFB made with common foods including red rice, red lentils, and vegetable oil) from 4-12 mo had significantly greater weight gain from 4-12 mo than those receiving mom’s choice of CFB, but found no differences in length gain 4-12 mo of age. Virtanen et al. (16) found no significant differences between infants, who were randomly assigned to receive cow’s milk that was either standard-fat, low-fat, or iron-fortified with either 50% vegetable fat and vitamin C, or 100% vegetable fat, with respect to weight at 18 mo, or weight change from 12-18 mo of age. Almquist-Tangen et al. (21) found that MCD at 6 mo of age, but not porridge or semi-solid foods, was significantly associated with high BMI (>1SD) at 12 mo and 18 mo of age. However, several potential key confounders were not adjusted for in analyses (SES, race/ethnicity, feeding practices) and no other outcomes were examined that could inform the results. For instance, it is unknown whether high BMI was driven by gains in FM or weight or decreases in length percentiles. Carruth et al. (27) reported that consumption of meat, mixed food, and/or table food by age 8 mo was associated with a smaller weight change from age 2-8 mo, although this did not remain significant after adjusting for length slope. Ianotti et al. (36) reported no differences between infants consuming animal source foods (meat, fish, egg, or milk) or other CFB (cereal, mixed or blended foods, stews, bread or other cereal products) from 6-12 mo of age with respect to MUAC, weight, length, or HC from 1-12 mo of age. Kalies et al. (37) reported a significantly lower risk of elevated weight gain (difference between weight at birth and at 24 mo of age) among infants consuming ‘ready-made’ vs. ‘self-made’ foods and ‘mixed CFB’ vs. ‘self-made’ foods. Santorelli et al. (43) found no significant association between intake of non-sweetened solid foods (e.g., baby rice, pureed vegetables, fruits or rice, and lentils/dhal) or sweetened foods (e.g. egg custard, rice pudding, sweetened rusks, biscuits and cake) and BMIZ at 3 y of age. Wosje et al. (48) found no significant differences between those consuming whole-milk vs. 2% fat milk with respect to (absolute or change in) weight, length, and body fat from 12-24 mo of age.

Amount of Other CFB. Two articles from one observational study mentioned previously (32, 33) examined intake in quintiles by weight and % total energy of additional CFB at 18 mo of age including dairy foods (milk, yogurt, cheese, ice cream, custard), milk (skim, whole and evaporated), fruits, vegetables, total extra foods (e.g., savory sauces, fats, and oils), fried potatoes, salty snacks (e.g., cheese snacks, corn chips), confectionary (e.g., chocolate, jellies), cereal foods, including bread, pasta, rice, and breakfast cereals and cereal-based products (e.g., cookies, cakes). In terms of significant findings, negative associations were identified between the amount of cereal-based products and dairy foods consumed and BMI at age 8 y. In addition, positive associations were identified between the amount of fruit intake and WC at 8 y of age. Although they did not reach significance, there were trends suggesting that greater intake of vegetables was associated with higher BMI at 8 y whereas greater intake of confectionary foods was associated with lower BMI at 8 y. The amount consumed of other remaining foods (e.g., milk, cereal-foods, fried potatoes; salty snacks) were not significantly associated with BMI in either analysis (32, 33).

Other CFB introduction. Three articles from one observational study (Generation R) examined the age of introduction to fruit or vegetable snacks (22, 29, 30). Two articles found no significant associations between fruit or vegetable snack introduction and body composition (22, 29). Durmus et al. (30) found that fruit or vegetable snack introduction at 4-5 mo relative to >5 mo was significantly associated with greater thickness (total FM) at age 24 mo. Durmus et al. (30) found no other associations between introduction at <4, 4-5, or >5 mo and other outcomes including total, peripheral, or central FM at 24 mo or odds of overweight or obesity at 6 y of age.

Kramer et al. (38) found that intake of “other solids” (not described) at age 9 mo was associated with significantly lower LAZ from 9-12 mo of age but found no association with WLZ, WAZ, or HC at any age interval. Carruth et al. (27) reported that age of vegetable introduction was associated with lower weight change from age 2-8 mo in the final predictive model, although this did not remain significant after adjusting for length slope. Schack-Nielsen et al. (44) reported that later introduction of vegetables and firm food were significantly associated with decreased risk of overweight at 42 y but not with BMI at 20-34 y. Later introduction of vegetables was associated with decreased BMI at 20–34 y and 42 y. Associations between egg introduction (continuous) and overweight at ages 20–34 y or 42 y were not significant. Introduction of firm food (bread and biscuits mixed with milk) was negatively associated with BMIZ at age 1 y, 10 y and 11 y but this did not persist at 42 y. Later introduction of spoon-feeding (continuous) was not associated with risk of overweight at 42 y but was significantly associated with lower BMI at 42 y and smaller WC at 42 y. When examined categorically, there was a non-significant trend for later introduction (≥ 4 vs. <4 mo) of spoon-feeding to be associated with decreased risk of overweight at 42 y. Schack-Nielsen et al. (44) also found no significant associations between number of food items from the CFB groups at ages 3, 4, 5, or 6 mo and risk of overweight at 42 y. Zheng et al. (49) reported that introduction to fish liver oil <3 vs. at 4-6 mo was significantly associated with increased risk of overweight at 4-5 y, but not obesity at 4-5 y. There were no significant associations between introduction to other CFB examined in that study (e.g., egg yolk, liver paste, tofu) and risk of overweight or obesity at 4-5 y of age (49).

Table 5 Studies that examined other CFB and growth, size, and body composition

Reference^1^, country, analytic N | Independent variable/exposure^2^ | Results for weight status | Results for body composition | Results for weight | Results for length/height | Results for circumference
Almquist-Tangen et al., 2013 (Almquist-Tangen, 2013); Sweden; N: 2,404 12mo; 2,241 18mo | Milk cereal drink , Y/N at age 6mo | High BMI: at 12mo OR=1.66, 95%CI: 1.07-2.57, P=0.02; at 18mo OR=1.58 95%CI: 1.04-2.39, P=0.03
Almquist-Tangen et al., 2013 (Almquist-Tangen, 2013); Sweden; N: 2,404 12mo; 2,241 18mo | Porridge intake, Y/N at age 6mo | High BMI at 12 or 18mo, NSA
Almquist-Tangen et al., 2013 (Almquist-Tangen, 2013); Sweden; N: 2,404 12mo; 2,241 18mo | Semi-solids intake, Y/N at age 6mo | High BMI at 12 or 18mo, NSA
Ay et al., 2008 (22); Netherlands; N: 1012 | Fruit snack introduction: <5 or >5mo | | Skinfold thickness at 24mo, NSA
Carruth et al., 2000 (27); U.S.; N: 94 | Food cluster present by age 8mo: any meat, mixed foods or table foods | | | Weight change 2-8mo, β=−0.1755, P=0.0324 but final model, NSA
Carruth et al., 2000 (27); U.S.; N: 94 | Vegetable introduction, continuous | | | Weight change 2-8mo, β=−0.0567, P=0.0457 but final model, NSA
de Silva et al., 2007 (19); Non-RCT; Sri Lanka; N: 152 | Intervention: home-based CFB + recipes + mechanical blender from age 4-12mo vs. Control: CFB of mothers’ choice from age 4-12mo | | | Weight gain 4-12mo: 2.43, SD=0.72kg vs. 2.02; SD=0.62kg, P=0.0002 | Length gain 4-12mo, NSGD
Durmus et al., 2012 (30); Netherlands; N: 779 | Fruit or vegetable snack introduction: 4-5 vs. >5mo | | Total, peripheral or central FM at 6mo, NSA; Total FM at age 24mo, β=1.46, 95%CI: 0.05, 2.88, P<0.05; Peripheral or central FM at 24mo, NSA
Durmus et al., 2012 (30); Netherlands; N: 779 | Fruit or vegetable snack introduction: <4 vs. >5mo | | Total, peripheral or central FM at 6 or 24mo, NSA
Durmus et al., 2014 (29); Netherlands; N: 5063 | Fruit or vegetable snack introduction: <4, 4-4.9, ≥5mo | Overweight or obesity at 6y, NSA | Total FM, android-gynoid fat ratio, abdominal fat, or BMI at 6y
Garden et al., 2011 (33); Australia; N: 362 (WC: 339) | Dairy products: combined milk and milk product yogurt, cheese, ice cream, custard intake (g, % total energy) at age 18mo | | BMI at 8y, % energy, β=−0.21; 95% CI:−0.41, −0.01; P=0.04; g, NSA; WC at 8y, NSA
Garden et al., 2011 (33); Australia; N: 362 (WC: 339) | Milk: skim, whole, and evaporated intake (g, % total energy) at age 18mo | | BMI at 8y, NSA; WC at 8y, NSA
Garden et al., 2011 (33); Australia; N: 362 (WC: 339) | Fruit intake (g, % total energy) at age 18mo | | BMI at 8y, NSA; WC at 8y, g β=0.63; 95% CI: 0.05, 1.2, P=0.03; % total energy β=0.56, 95% CI: 0.00, 1.1, P=0.05
Garden et al., 2011 (33); Australia; N: 362 (WC: 339) | Vegetables intake (g, % total energy) at age 18mo | | BMI at 8y , g B=0.20; 95% CI:0.00, 0.40; Trend P=0.05, NSA; % energy, NSA; WC at 8y, NSA
Garden et al., 2011 (33); Australia; N: 362 (WC: 339) | Cereal-foods: bread, pasta, rice, breakfast cereals, etc. intake (g, % total energy) at age 18mo | | BMI at 8y, NSA; WC at 8y, NSA
Garden et al., 2011 (33); Australia; N: 362 (WC: 339) | Total Extra foods: savory sauces, fats, and oils, etc. intake (g, % total energy) at age 18mo | | BMI at 8y, NSA; WC at 8y, NSA
Garden et al., 2011 (33); Australia; N: 362 (WC: 339) | Fried Potatoes intake (g, % total energy) at age 18mo | | BMI at 8y, NSA; WC at 8y, NSA
Garden et al., 2011 (33); Australia; N: 362 (WC: 339) | Salty snacks: potato crisps, cheese snacks, corn chips intake (g, % total energy) at age 18mo | | BMI at 8y, NSA; WC at 8y, NSA
Garden et al., 2011 (33); Australia; N: 362 (WC: 339) | Confectionary Foods: chocolate, jellies, energy bars intake (g, % total energy) at age 18mo | | BMI at 8y, β=−0.25, 95% CI: −0.49, 0.00, Trend P=0.05, NSA; WC at 8y, NSA
Garden et al., 2011 (33); Australia; N: 362 (WC: 339) | Cereal-based products: cookies, cakes, pies, buns, etc. intake (g, % total energy) at age 18mo | | BMI at 8y, g: β=−0.23, 95% CI:−0.44, −0.22, P=0.03; % Energy, β=−0.27; 95% CI:−0.47, −0.07, P=0.01; WC at 8y g β=−0.61; 95% CI: −1.17, −0.05, P=0.03; % energy, β=−0.76, 95% CI: −1.29, −0.23, P=0.01
Garden et al., 2012 (32); Australia; N: 298 | Dairy products: combined milk and milk product yogurt, cheese, ice cream, custard intake (g, % total energy) at age 18mo | | BMI trajectory birth-11.5y in boys or girls, NSA
Garden et al., 2012 (32); Australia; N: 298 | Milk: skim, whole, and evaporated intake (g, % total energy) at age 18mo | | BMI trajectory birth-11.5y in boys or girls, NSA
Garden et al., 2012 (32); Australia; N: 298 | Fruit intake (g, % total energy) at age 18mo | | BMI trajectory birth-11.5y in boys or girls, NSA
Garden et al., 2012 (32); Australia; N: 298 | Vegetables intake (g, % total energy) at age 18mo | | BMI trajectory birth-11.5y in boys or girls, NSA
Garden et al., 2012 (32); Australia; N: 298 | Cereal-foods: bread, pasta, rice, breakfast cereals, etc. intake (g, % total energy) at age 18mo | | BMI trajectory birth-11.5y in boys or girls, NSA
Garden et al., 2012 (32); Australia; N: 298 | Total Extra foods: savory sauces, fats, and oils, etc. intake (g, % total energy) at age 18mo | | BMI trajectory birth-11.5y in boys or girls, NSA
Garden et al., 2012 (32); Australia; N: 298 | Fried Potatoes intake (g, % total energy) at age 18mo | | BMI trajectory birth-11.5y in boys or girls, NSA
Garden et al., 2012 (32); Australia; N: 298 | Salty snacks: potato crisps, cheese snacks, corn chips intake (g, % total energy) at age 18mo | | BMI trajectory birth-11.5y in boys or girls, NSA
Garden et al., 2012 (32); Australia; N: 298 | Confectionary Foods: chocolate, jellies, energy bars intake (g, % total energy) at age 18mo | | BMI trajectory birth-11.5y in boys or girls, NSA
Garden et al., 2012 (32); Australia; N: 298 | Cereal-based products: cookies, cakes, pies, buns, etc. intake (g, % total energy) at age 18mo | | BMI trajectory birth-11.5y in boys or girls, NSA
Iannotti et al., 2009 (36); Peru; N: 232 | CFB vs. CFB from animal sources (i.e., meat, fish, egg, or milk) at age 6-12mo | | Skinfolds from 6-12mo or MUAC from 1-12mo, NSA | Weight 1-12mo, NSA | Length 1-12mo, NSA | HC 1-12mo, NSA
Kalies et al., 2005 (37); Germany; N: 2,337 | Mixed CFB vs. Self-made CFB | | | Weight gain at 24mo, NSA
Kalies et al., 2005 (37); Germany; N: 2,337 | Ready-made CFB vs. Self-made CFB | | | Weight gain at 24mo: OR 0.56, 95%CI: 0.39, 0.81, P=NR
Kramer et al., 2004 (38); Belarus; N: 17,046 | Other solids intake, any vs. none at ages 1, 3, 6, or 9mo | | WLZ 1-3, 3-6, 6-9, and 9-12mo of age, NSA | WAZ from 1-3, 3-6, 6-9, 9-12mo of age, NSA | LAZ from age 9-12mo: β=−0.082, 95% CI: −0.156, −0.008, P=NR; 1-3, 3-6, 6-9mo, NSA | HC from 1-3, 3-6, 6-9, or 9-12mo of age, NSA
Liu et al., 1993 (8); RCT; China; N: 164 | Fortified Rusk: fortified (Fe, Zn, vit. A, calcium, folic acid) biscuit, 1/d for 3mo, ages 6-16mo vs. Unfortified Rusk: unfortified biscuit 1/d for 3mo, ages 6-16mo | | | Weight or increase in weight at ages ~9-16mo, NSGD | Length or increase in length, at ages ~9-16mo, NSGD
Lind et al., 2004 (7); RCT; Sweden; N: 263 | Regular-phytate group: commercial MCD from oat and wheat flours mixed with milk powder and Fe-fortifed, at ages 6 to 12 mo; Reduced-phytate group: phytate-reduced MCD from white-wheat flour and porridge from age 6-12 mo; Infant formula group: milk-based infant formula and porridge | | | WAZ at 6, 12, 18 mo, NSGD | LAZ at 6, 12, 18 mo, NSGD | HC at 6, 12, 18 mo, NSGD; MUAC at 6, 12, 18 mo, NSGD
Santorelli et al., 2014 (43); U.K.; N: 1327 | Non-sweetened solid foods introduction: baby rice, pureed vegetables, fruits or rice, and lentils/dhal | | BMIZ at 3y, NSA
Santorelli et al., 2014 (43); U.K.; N: 1327 | Sweetened foods introduction: egg custard, rice pudding, sweetened rusks, biscuits and cake (plus non-sweetened foods when given together) | | BMIZ at 3y, NSA
Schack-Nielsen et al., 2010 (44); Denmark; N: 5068 | Spoon-feeding introduction, continuous | At 42y, overweight, NSA; obesity, NSA | BMI ages: 1-34y, NSA; 42y, β=−0.046, 95%CI: −0.86, −0.006, P=0.03; WC at 42y, −0.25 cm/mo, 95% CI −0.49, −0.01
Schack-Nielsen et al., 2010 (44); Denmark; N: 5068 | Spoon-feeding introduction, ≥4 vs. <4mo | Lower risk of overweight at 42y, P=0.053
Schack-Nielsen et al., 2010 (44); Denmark; N: 5068 | Vegetable introduction, continuous | At 42y, overweight, OR 0.90, 95%CI: 0.81, 0.98, P=0.014; obesity, NSA | BMIZ at ages: 20–34y, β=−0.072; 95% CI −0.133, −0.010; 42y, β=−0.064; 95%CI: −0.101, −0.027
Schack-Nielsen et al., 2010 (44); Denmark; N: 5068 | Vegetable introduction, ≥4 vs. <4mo | Lower risk of overweight at 42y, P=0.046
Schack-Nielsen et al., 2010 (44); Denmark; N: 5068 | Egg introduction, continuous | At 42y, overweight, NSA; obesity, NSA | BMI at 20-34y or 42y, NSA
Schack-Nielsen et al., 2010 (44); Denmark; N: 5068 | Egg introduction, ≥4 vs. <4mo | Overweight at 42y, NSA
Schack-Nielsen et al., 2010 (44); Denmark; N: 5068 | Firm food introduction, continuous | At 42y, overweight, OR 0.92, 95%CI: 0.86, 0.98, P=0.012; obesity, NSA | BMIZ at ages: 1y, β=−0.053, 95%CI: −0.082, −0.024; 10y, β=−0.054, 95%CI: −0.096, −0.012; 11y, β=−0.057, 95%CI: −0.101, −0.0103; 20-34y or 42y, NSA
Schack-Nielsen et al., 2010 (44); Denmark; N: 5068 | Firm food introduction, ≥4 vs. <4mo | Overweight at 42y, NSA
Schack-Nielsen et al., 2010 (44); Denmark; N: 5068 | # of food items at 3, 4, 5, 6mo | Overweight at 42y, NSA
Virtanen et al., 2001 (16); RCT; Sweden; N: 36 | Cow’s milk: Low-fat or standard-fat, ad libitum at age 12-18mo vs. Fe-fortified cow’s milk: ferrous gluconate-fortified with 50% vegetable fat or ferrous lactate-fortified with 100% vegetable fat, ad libitum at age 12-18mo | | | Weight at 18mo,NSGD; weight change from 12-18mo, NSGD
Wosje et al., 2001 (48); U.S.; N: 51 | 2% cow’s milk vs. whole at age 12mo | | % body fat, % body fat z score, % body fat gain, or change in % body fat z-score from 12-24mo, NSA | Weight, weight z-score, weight gain, or change in weight z-score from 12-24mo, NSA | Length, length z score, length gain, or change in length z score from 12-24mo, NSA
Zheng et al., 2015 (49); China; N: 40,510 | Fish liver oil introduction, ≤3 vs 4-6mo | Overweight at 4-5y, OR 1.08, 95%CI: 0.99, 1.17, P=0.004; Obesity, NSA | Higher BMI at 4-5y, P<0.001
Zheng et al., 2015 (49); China; N: 40,510 | Fish liver oil introduction, 4-6 vs. >6mo | Overweight at 4-5y, NSA; Obesity at 4-5y, NSA | BMI at 4-5y, NSA
Zheng et al., 2015 (49); China; N: 40,510 | Egg yolk introduction, ≤3 vs 4-6mo | Overweight at 4-5y, NSA; Obesity at 4-5y, NSA | Lower BMI at 4-5y, P=0.046
Zheng et al., 2015 (49); China; N: 40,510 | Egg yolk introduction, 4-6 vs. >6mo | Overweight at 4-5y, NSA; Obesity at 4-5y, NSA | BMI at 4-5y, NSA
Zheng et al., 2015 (49); China; N: 40,510 | Other foods introduction, ≤3 vs 4-6mo or 4-6 vs. >6mo: fish paste, liver paste, tofu, bread/steamed bun/fine dried noodle, or pureed noodle/cookies | Overweight at 4-5y, NSA; Obesity at 4-5y, NSA | BMI at 4-5y, NSA

1 All studies, except those noted as RCT or non-RCT, followed a prospective cohort design

2 The independent variable/exposure of interest included types and/or amounts of CFB, which encompassed dietary patterns during the complementary feeding period and timing of specific CFB; this section of studies examined various other CFB that did not fit into previously labeled sections such as milk and/or dairy products, vegetables, fruits, egg, and categories such as “ready-made” or “animal source” foods.

3 Outcomes were organized for practicality into columns: weight status, body composition, weight, length or height, and head circumference. Results described in the respective columns are based on outcome similarity and in accordance with the analytical framework as follows: Weight status included risk/incidence/prevalence/frequency of malnutrition, healthy weight, overweight, or obesity; Body composition included measures, indices, and proxies of overall adiposity such as lean mass, fat mass (FM), % body fat, weight-to-height ratios such as BMI, BMIZ, WLZ, central adiposity or waist circumference, and arm or thigh circumferences; Weight included weight-specific measures such as weight-for-age z-score (WAZ), Length or Height included length-specific measures such as length-for-age z-score (LAZ); Head circumference included head circumference

Abbreviations: BF, breast-fed; CFB, complementary food/beverage; Fe, iron; FF, formula-fed; FM, fat mass; LAZ, length for age z-score; MUAC, mid-upper arm circumference; NR, not reported; NSA, no significant association; NSGD, no significant group differences; RCT, randomized controlled trial; WC, waist circumference; WAZ, weight for age z-score; WLZ, weight for length z-score; Zn, zinc

#### Dietary patterns

Eleven articles examined distinct dietary patterns during the CF period, including one RCT (12) and 10 articles from observational studies (20, 23–25, 28, 34, 41, 42, 46, 47). Dietary patterns at different ages from the same cohort were analyzed in multiple articles as follows: Infant Feeding Practices Study (42, 47) and the Southampton Women’s Survey (23, 41) (see Table 6).

Seven articles from observational studies identified various associations between the dietary patterns examined and growth, size, body composition and/or overweight or obesity status outcomes (23, 28, 34, 41, 42, 46, 47). Results reported in these seven articles are summarized below briefly. Table 6 provides details regarding the specific dietary patterns that were compared and additional information can be found in Supplemental Table 1.

Baird et al. (33) found that adherence to the ‘Infant guidelines’ pattern at age 6 mo was associated with significantly greater conditional gains in weight and skinfold thickness from 6-12 mo and greater absolute skinfold thickness at 12 mo of age. Infants who were in the highest compared to lowest quartile for scores on the U.K. ‘Infant guidelines’ pattern at 6 mo gained ~0.12kg more weight and ~0.49mm more in skinfold thickness from 6-12 mo of age. Greater adherence to the ‘Adult foods’ pattern at 6 mo was significantly associated with lower weight gain from 6-12 mo of age but not with skinfold thickness (at age 12 mo or gain from 6-12 mo). There were no significant associations between either dietary pattern at 6 mo and weight or length at 12 mo or change in length from 6-12 mo of age.

Robinson et al. (51) reported that greater adherence to the U.K. ‘Infant guidelines’ pattern at age 12 mo was significantly associated with increased lean mass and lean mass index, but not with BMI, FM, or FMI at 4 y of age.

Rose et al. (52) used latent class analysis to assign infants based on frequency of intake to one of five dietary patterns described in Table 6. Outcomes were assessed based on maternal-report of height and weight. Rose et al. (52) reported that infants in the ‘MXHED’ group had the highest prevalence of overweight at 1 y of age compared to all other classes. The ‘MXHED’ and ‘FFLV’ groups had significantly higher WLZ at 1 y than other classes (‘BFLV’, ‘BFFV’, or ‘FFFV’).

Wen et al. (57) assigned adherence scores to each infant for four dietary patterns at age 6 mo, identified via principal component analysis. Outcomes were assessed based on reported weight and height. Wen et al. (57) found no significant association between adherence to the U.S. ‘Infant guideline solids’ pattern at 6 mo and change in BMIZ from 6-12 mo. However, greater adherence to the other three patterns at 6 mo was associated with greater change in BMIZ from 6-12 mo. Both the ‘High dairy/regular cereal’ and ‘High sugar/fat/protein’ patterns were associated with smaller increases in LAZ from age 6-12 mo.

Golley et al. (44) assigned each infant a CF utility index (CFUI) score at age 6 mo, which was derived and analyzed from dietary pattern scores as a continuous variable from 14 components such as BF duration, age of introduction to solids, textured foods, and minimizing ready-made infant foods. Higher CFUI scores reflected higher adherence to U.K. guidelines for CF. Golley et al. (44) reported that higher CFUI scores at 6 mo were not associated with BMI at 7 y of age but were (weakly) associated with smaller WC at 7 y.

Two articles (28, 46) from observational studies reported similar relationships between dietary patterns and wasting (defined according to arm-muscle-area, which was calculated from MUAC and triceps skinfold thickness) and/or malnutrition (defined as WAZ, LAZ, and/or WLZ of less than 2 SD, respectively underweight, stunting, or wasting, according to Thai references). Dagnelie and Staveren found that a ‘Macrobiotic’ diet compared to ‘Omnivorous’ diet at age 4-18 mo (see Table 6) was significantly associated with higher wasting, lower weight-for-length, lower weight velocity, lower length velocity, lower MUAC velocity, lower arm muscle area velocity, and lower HC velocity (37). However, there were no significant differences in crown-rump length velocity, triceps or subscapular skinfold thickness velocities (mm/y), biiliacal width velocity (cm/y), or arm fat area velocity (mm^2^/y). Tantrecheewathorn reported that ‘Inadequate’ compared to ‘Adequate’ diets (see Table 6) were significantly associated with increased relative risk of malnutrition, defined as either underweight, stunted, or wasted (55).

Four articles reported no significant associations between dietary patterns (observed, or derived by analyses) during the CF period and growth, size, and body composition outcomes (12, 20, 24, 25). Results showed no significant differences between the respective dietary patterns examined in each study and the following outcomes examined: (mean or change in) weight, length, HC, or MUAC at 6-12 mo of age (21), overweight/obesity status at 45-48mo (29); body composition, weight, or length at 4-6 mo (ref 33); or body composition at age 24 mo (34).

Table 6 Studies that examined dietary patterns during the complementary feeding period and growth, size, and body composition

Reference^1^, country, analytic N | Dietary patterns^2^ | Comparison | Results for weight status | Results for body composition | Results for weight | Results for length/height | Results for head circumference
Abraham et al., 2012 (20); Scotland; N: 4493 | Two dietary patterns were identified at age 19-24mo:; ‘Negative pattern’: low fruit, vegetable; high sweets, crisps, soft drinks, snacking; ‘Positive pattern’: high fruit, vegetable; low snacking | ‘Negative’ vs. ‘Positive’ pattern | Overweight or obese at 45-48mo, NSA
Baird et al., 2008 (23); U.K.; N: 1740 | Two dietary patterns were identified at age 6mo:; 1) ‘Infant guidelines’: high frequency of consumption of vegetables, fruit, meat, fish, home-prepared foods, breast milk; low frequency of consumption of commercial baby foods in jars and formula | Higher vs. lower quintiles for ‘Infant guidelines’ | | Gain in skinfold age 6-12mo, β=0.11, 95%CI: 0.04, 0.18, P=0.002; corresponding to 0.26 SDS; Skinfold thickness at 12mo, β=0.13, 95%CI: 0.01, 025, P=0.03 | Gain in weight age 6-12mo, β=0.10, 95%CI: 0.04, 0.17; P=0.002, corresponding to 0.24 SDS; Weight at 12mo, NSA | Gain in length age 6-12mo, NSA; Length at 12mo, NSA
Baird et al., 2008 (23); U.K.; N: 1740 | 2) ‘Adult foods’: high frequency of consumption of bread, savory snacks, biscuits, squash, breakfast cereals, and crisps; low frequency of breast milk, baby rice, and cooked and canned fruit | Higher vs. lower quintiles for ‘Adult foods’ | | Gain in skinfold age 6-12mo, NSA; Skinfold thickness at 12mo, NSA | Gain in weight age 6-12mo, β=−0.08, 95%CI: −0.15, −0.02, P=0.0015; Weight at 12mo, NSA | Gain in length age 6-12mo, NSA; Length at 12mo, NSA
Barton et al., 2002 (24); U.S.; N: 52 | Two dietary patterns were observed at age ≤4-6mo:; ‘Inappropriate foods’: home-prepared mashed potatoes and gravy, green beans with fat-back, pork, bacon, steak, high-sugar high-fat puddings, desserts, soda, and juice >6oz/d; ‘Appropriate foods’: Parent-prepared solids w/o extra fat, salt, sugar | ‘Inappropriate’ vs. ‘Appropriate’ | | | Weight at 4-6mo, NSA | Length at 4-6mo, NSA | HC at 4-6mo, NSA
Bell et al., 2013 (25); Australia; N: 493 | Four dietary patterns were identified at age 13-16mo:; ‘Core’: fruit, grains, nonwhite bread, vegetables, cheese, eggs, nuts and seeds; ‘Basic combination’: basic core + non-core w/o fruit or vegetables; ‘Basic core’: white bread, milk; ‘Non-core’: spreads, juice, ice-cream | Each pattern relative to outcomes | | BMIZ at 24mo, NSA
Dagnelie and van Staveren, 1994 (28); Netherlands; N: 106 | Two dietary patterns were observed at ages 4-10mo; ‘Macrobiotic diet’: Included unpolished rice, pulses and vegetables with a high fiber content, small additions of seaweeds, fermented foods, nuts, seeds, and seasoned foods; Avoided vit. D supplements, products of animal origin such as meat and dairy product, fat/oil, and fish.; ‘Omnivorous diet’: Not described | ‘Macrobiotic ‘vs. ‘Omnivorous’ | Wasting 30% vs. 2%, P<0.001 | MUAC velocity, 1.0 vs. 2.3 cm/y, P < 0.01; Smaller arm muscle area velocity, 413 vs. 624 mm^2^/y, P < 0.01; Slower weight-for-length, P<0.05. Triceps or subscapular skinfold thickness velocities, NSA; biiliacal width velocity, NSA; arm fat area velocity, NSA | Weight velocity, 3.3 vs. 4.4 kg/y, P<0.001 | Length velocity, 13.2 vs. 16.7 cm/y, P<0.001; Crown-rump length velocity, NSA | Lower HC velocity, 5.2 vs. 6.1cm/y. P < 0.05
Golley et al., 2013 (34); U.K.; N: 7834 | Each infant received a CFUI score at age 6mo, derived and analyzed as a continuous variable from 14 components such as BF duration, textured foods, and minimizing ready-made infant foods | CFUI scores (higher scores reflected higher adherence to CF guidelines) | | BMI at 7y, NSA; WC at 7y: β=−0.15, 95% CI: −0.31, −0.002, P=0.046
Olaya et al., 2013 (12); RCT; Colombia; N: 76 | Intervention group: individual, face-to-face nutrition counseling with 3 key messages, 1) the importance of continuing BF alongside CFB, 2) red meat as a source of Fe to prevent anemia (>5 portions/wk, red meat, chicken liver and heart), and 3) daily fruit and vegetables as part of a healthy diet from ages 6-12mo; Control group: standard CF advice from health care professionals on meat consumption, but no advice on frequency or amount of foods was given, from ages 6-12mo | Intervention vs. Control | | MUAC at 12mo, NSGD; Change in MUAC 6-12mo, NSGD | Mean WAZ at 12mo, NSGD; Change in WAZ 6-12mo, NSGD | Mean LAZ at 12mo, NSGD; Change in LAZ 6-12mo, NSGD | HC at 12mo, NSGD; Change in HC 6-12mo, NSGD
Robinson et al., 2009 (Robinson, 2009); U.K.; N: 536 | One dietary pattern was identified at age 12mo:; ‘Infant guidelines’ pattern: High consumption of fruit, vegetables, cooked meat and fish, and other home-prepared foods (rice, pasta), and low consumption of commercial baby foods | Higher vs. lower ‘Infant guidelines’ . scores | | Increased lean mass at 4y, P=0.003; Increased lean mass index at 4y, P=0.004; BMI, FM, or FMI at 4y, NSA
Rose et al., 2016 (42); U.S.; N: 1029 | Five dietary patterns were identified at age 9mo:; BFFV, ‘Breastfed Fruits and Vegetables’: Breastmilk, fruits, and vegetables, and low intake of energy-dense foods; BFLV, ‘Breastfed Low Variety’: Breastmilk, and low intake of fruits and vegetables, low diet variety; FFFV, ‘Formula-Fed Fruits and Vegetables’: Formula, fruits, and vegetables, and low intake of energy-dense foods; FFLV, ‘Formula-Fed Low Variety’: Formula, and low intake of fruits and vegetables, low diet variety; MXHED, ‘Mixed High Energy Density’: Breastmilk and formula, low intake of fruits and vegetables, diet variety, and higher intake of energy-density foods (e.g. french fries, sweet foods) | Each pattern relative to outcomes | Prevalence of overweight at 1y highest for MXHED relative to prevalence for BFFV, BFLV, FFFV, FFLV, values NR | WLZ at 1y: BFFV: 0.09; BFLV: −0.02; FFFV: 0.47; FFLV: 0.70, MXHED: 0.74, P<0.01 | WAZ at 1y: BFFV: −0.30; BFLV: −0.60; FFFV: −0.06; FFLV: −0.11, MXHED: −0.10. P<0.001
Tantracheewathorn, 2005 (46); Thailand; N: 140 | Two dietary patterns were observed prior to age 12mo:; ‘Adequate’ CFB: consumed a variety of food from various food groups (rice and grains, fruits, vegetables, milk, meat, eggs, fat), and adequate amounts of nutrient and energy compared with Thai Recommended Dietary Allowances; ‘Inadequate’ CFB: not described | ‘Inadequate’ vs. ‘Adequate’ | Malnutrition, OR 4.7, 95%CI: 1.1, 21.9, P=0.04
Wen et al., 2014 (47); U.S.; N: 530 | Four dietary patterns were identified at age 6mo:; ‘Infant guideline solids’: Baby cereal, fruit, vegetables, meat/chicken; ‘High sugar/fat/protein’: Sweet drinks, french fries, fish/shellfish, nut foods, eggs, sweet foods; ‘High dairy/regular cereal’: Cow’s milk, other dairy, 100% juice, non-baby cereals/starches; ‘Formula’: Formula, low intakes of breast milk | Each pattern relative to outcomes | | Change in BMIZ from age 6-12mo: High sugar/fat/protein pattern: β=1.00, 95%CI: 0.11, 1.89; Infant guideline solids: β=0.06, 95%CI: −0.09, 0.22; Formula β=0.25, 95%CI: 0.09, 0.40; High dairy/regular cereal β=0.32, 95%CI: 0.10, 0.53 | | Change in LAZ from age 6-12mo, High sugar/fat/protein pattern: β=−1.36, 95%CI: −2.35, −0.37; Infant guideline solids: β=0.12, 95%CI: −0.05, 0.29; Formula β=0.01, 95%CI: −0.16, 0.18; High dairy/regular cereal β=−0.30, 95%CI: −0.54, −0.06

1 All studies, except those noted as RCT or non-RCT, followed a prospective cohort design

2 The independent variable/exposure of interest included types and/or amounts of CFB, which encompassed dietary patterns during the complementary feeding period and timing of specific CFB; The studies in this section examined dietary patterns classified by observation or statistical analyses (e.g., adherence scores derived from latent class, cluster, or principal component analysis)

3 Outcomes were organized for practicality into columns: weight status, body composition, weight, length or height, and head circumference. Results described in the respective columns are based on outcome similarity and in accordance with the analytical framework as follows: Weight status included risk/incidence/prevalence/frequency of malnutrition, healthy weight, overweight, or obesity; Body composition included measures, indices, and proxies of overall adiposity such as lean mass, fat mass (FM), % body fat, weight-to-height ratios such as BMI, BMIZ, WLZ, central adiposity or waist circumference, and arm or thigh circumferences; Weight included weight-specific measures such as weight-for-age z-score (WAZ), Length or Height included length-specific measures such as length-for-age z-score (LAZ), linear velocity; Head circumference included head circumference.

Abbreviations: BF, breast fed; BFFV, breast fed fruits and vegetables pattern; BFLV, breast fed low variety pattern; CFB, complementary food/beverage; CFUI, complementary feeding utility index; Fe, iron; FF, formula-fed; FFFV, formula-fed fruits and vegetables pattern; FFLV, formula-fed low variety pattern; FM, fat mass; FMI, fat mass index; LAZ, length for age z-score; MUAC, mid-upper arm circumference; MXHED, mixed high energy density pattern; NR, not reported; NSA, no significant association; NSGD, no significant group differences; RCT, randomized controlled trial; SSB, sugar-sweetened beverage; WC, waist circumference; WAZ, weight for age z-score; WLZ, weight for length z-score

### Discussion

#### Meat

Moderate evidence indicates that higher versus lower meat intake or meat versus Fe-fortified cereal intake over a short duration (~3 mo) during the CF period does not favorably or unfavorably influence growth, size, or body composition. There is insufficient evidence to determine a relationship between meat intake and prevalence/incidence of overweight or obesity. Despite the majority of evidence coming from well-designed RCTs, these studies were not necessarily designed to determine the effects of adequate or inadequate amounts of meat consumption on growth-related outcomes. For example, the objective of Yeung and Zlotkin (18) was to prevent iron depletion in cow’s milk-fed infants by testing CFBs that are higher in iron content, and collected anthropometric measurements mainly to ensure that growth was not impaired during the trial. Among the trials, there are several important methodological limitations such as short durations ~3 mo, variable length of follow-up, relatively small sample sizes, insufficiently described data, statistical analyses, and/or outcome assessment methods. Findings from one study in China may be less generalizable due to participants coming from a rural community with high rates of stunting (15). All of the RCTs reported outcomes prior to 18 mo of age and therefore do not provide information on growth, size, or body composition later in childhood.

Five studies (two RCTs and three observational studies) examined the amount of meat given and BMI only, weight only, or weight and other outcomes. Neither of the trials assessed the impact of high loss to follow-up or provided sufficient detail to determine the reliability/validity of outcome assessment (2, 3)and did not adjust for baseline differences between groups (3), or did not report results for all potential outcomes (2). Observational studies pointed to positive relationships between meat intake and outcomes but varied in terms of when meat intake was examined, how outcomes were assessed, and did not adjust analyses for potential key confounders (SES, maternal age, or gestational age).

#### Cereal

Limited evidence suggests that type or amount of cereal given does not favorably or unfavorably influence growth, size, body composition, and/or prevalence/incidence of overweight or obesity. Results from six studies (3 RCTs) provided little evidence of a strong relationship between the type or amount of cereal and the outcomes assessed. Studies varied considerably in the type or amount of cereal provided (e.g., wheat/soy vs. wheat/milk fortified weaning cereal; Fe-fortified vs. non-fortified cereal) and outcomes examined. Limitations include a lack of description regarding statistical methods, potential impact of unintended exposures due to other CFB consumed, indirectness, failure to adjust statistical analyses for multiple comparisons, and limited generalizability.

#### CFB with different fats/ fatty acid composition

Moderate evidence suggests that consumption of complementary foods with different fats and/or fatty acid composition does not favorably or unfavorably influence growth, size, or body composition although there is not enough evidence regarding overweight or obesity specifically. There was variation in the different CFB and/or fats/fatty acids tested (4, 6, 10, 13), with two studies examining egg-yolk as sources of DHA, one examining fish, and another examining a CFB meal with fatty-acids from different oil sources. None of the studies examined outcomes at ages older than 24 mo. Most of the articles lacked sufficient description of outcome assessment methods and therefore, the validity/reliability of outcomes could not be determined. Two articles did not account for high loss to follow-up (6, 13). One of the RCTs may not have been adequately powered to detect differences in growth (13).

#### SSBs

Limited evidence suggests that SSB consumption during the CF period is associated with increased risk of obesity in childhood, but is not associated with other measures of growth, size, and body composition. Two studies examined the relationship between SSB consumption during the CF period and risk of obesity in childhood. One of those two studies demonstrated significant increased risk of obesity in childhood and was weighed more heavily than the other study due to its strength including sample size and adjustment for potential confounders. Three studies examined the relationship between SSB consumption during the CF period and other outcomes (BMI, BMI trajectory, BMIZ, and WC) in childhood, with all finding no significant associations with these other measures. The relationship between early introduction of SSBs in the CF period and later childhood overweight or obesity could reflect unmeasured confounding factors. A stronger conclusion could not be drawn due to an inadequate number of studies (all were observational), inconsistencies in how SSBs were examined (e.g., age of introduction of SSBs), and lack of information on quantities consumed.

#### Juice drinks and 100% juice

Limited evidence suggested a significant positive association between juice intake and infant weight-for-length and child BMI z-scores. However, there is not enough evidence to determine the relationship between juice intake and other outcomes (i.e., growth, size, and/or body composition). The evidence came from only a few observational studies, most of which examined juice intake without describing the type of fruit or % of fruit juice in the juice, although one study specified orange juice or other 100% fruit juice (45). Notably, there were a few positive and significant associations observed between juice intake in relatively large amounts (e.g., 8-15 oz) or at young ages (e.g., at 9 mo) and WLZ, BMIZ, or WAZ. There was variation in types and age of outcomes assessed across studies, with most reporting weight relative to length outcomes (e.g., WLZ, BMI) at different ages. The reliability/validity of measures for outcome assessment could not be determined in several of these studies because weight and/or length was obtained from maternal report, unstandardized methods, or was not reported.

#### Other CFB

No conclusion could be made about the relationship between other CFB (vegetables, fruit, dairy products and/or cow’s milk, cereal-based products, milk-cereal drink, and/or categories such as “ready-made” foods) and growth, size, body composition, and/or prevalence/incidence of overweight or obesity. This was primarily due to heterogeneity in study design and the types of other CFB examined (e.g., distinct CFB such as cow’s milk, MCD, vegetables, fruit, tofu, biscuits/breads, and/or groupings such as dairy products, animal source foods, sweetened/confectionary foods, ‘mixed’ foods, and ‘ready-made’ foods). The majority of evidence was observational, although data were included from several RCTs and one non-RCT. There were also the following:

- limited generalizability to the U.S. population due to CFB used or CF practices at the time of the study,
- inadequacy of statistical methods regarding adjustment for multiple comparisons,
- indirectness with which some studies examined the link between types or amounts of other CFB and outcomes,
- variation in outcome types and assessment methods, and
- inconsistency in which analyses were adjusted for potential confounders (e.g., SES, race and/or ethnicity, feeding practices, or birth size).

#### Dietary patterns

No conclusion could be made about the relationship between distinct dietary patterns during the CF period and growth, size, body composition, or prevalence/incidence of malnutrition, overweight or obesity (Table 8). The conflicting evidence precludes the ability to draw a conclusion due to heterogeneous analyses of dietary patterns. The studies were difficult to compare and contrast due to the wide variation in the specific dietary patterns compared, as well as the outcomes assessed. In several cases, the labelling of dietary patterns carried judgement (e.g., ‘Inappropriate’ or ‘Inadequate’), which may or may not correspond to evidence-based infant feeding.

Several articles examined the relationship between dietary patterns that align with CF guidelines and growth, size, and/or body composition outcomes. Although some studies emphasized fruits, vegetables, and meats in a pattern labelled “Infant guidelines’, there were differences in other emphasized foods, such as baby cereal (56) or commercial baby food (50), across other patterns. Several articles identified dietary patterns that do not clearly align with CF guidelines and varied widely in specific foods or food groups included (e.g., high frequency of french fries, sweet foods, fish/shellfish, nut foods, and eggs (47) compared to bread, snacks, crisps, breakfast cereals and low frequency of human milk and cooked/canned fruit (23)).These prospective studies are likely confounded by unmeasured factors that may differ between families that follow infant feeding guidelines vs. those who do not. For example, families that adhere to infant feeding guidelines may choose healthier diets and lifestyles (e.g. physical activity) later in the child’s upbringing.

The results from Dagnelie and van Staveren (37) and Tantracheewathorn (55) are less generalizable to the U.S. population due to the types of dietary patterns examined (i.e., ‘Macrobiotic’ vs. ‘Omnivorous’; ‘Inadequate’ vs. ‘Adequate’). Neither of these observational studies adjusted for several confounding factors nor provided sufficient detail regarding comparison diets (e.g., ‘Omnivorous’; ‘Inadequate’). The relationship between dietary patterns during the CF period and overweight or obesity status was examined in two articles from observational studies, which varied in the specific dietary patterns assessed and reported inconsistent results.

### Limitations

Across the entire body of evidence, there were concerns surrounding methodological limitations and internal validity. One methodological limitation across most of the observational studies includes the potential for reverse causality. That is, the child may already be growing faster or slower when decisions regarding feeding frequency, types, or amounts of CFB are made. Another limitation includes the variability in controlling for confounding factors. While most studies did account for infant milk-feeding practices, the majority of observational studies (22 of 30) did not adjust for two or more key confounders (see Figure 1). Most of the RCTs enrolled infants who were EBF (4, 5, 11–15, 17) or EFF (1, 9) to 4 mo of age or older.

With few exceptions, the included studies were not designed to evaluate different amounts of CFB but rather varying types of CFB relative to outcomes. In addition, many studies were designed to test the influence of CFB in relation to outcomes other than those of interest in this SR. For example, several studies aimed to test the influence of Fe-fortified cereal on iron status, using anthropometric measures as secondary outcomes. In many cases, the amount of CFB provided would not be expected to affect growth and body composition over the duration in which it was tested. Several studies examined timing of specific types of CFB as opposed to more directly comparing different types and/or amounts of CFB in relation to growth outcomes (22, 26, 29, 30, 38, 43, 44, 49).

Most of the studies examined outcomes at multiple time points or assessed change over time to capture growth. However, a few trials (3, 6, 10) and many observational studies (20, 22, 25, 29, 31, 34, 41–43, 47–49) examined outcomes at only a single time point. Of those studies, all of the observational studies adjusted analyses for baseline or current anthropometric status (25, 29, 34, 47, 49), or birth weight (20, 31, 41–43, 49). Engelmann (3) reported differences between groups in baseline anthropometrics that were not accounted for in analyses. Both Libuda et al. (6) and Makrides et al. (10) lacked sufficient detail regarding outcome assessment, though Libuda et al. (6) reported no differences in birth weight between groups at baseline.

Another limitation is the limited reliability/validity of assessment methods for both outcome assessment and assessment of types and/or amounts of CFB. Several studies used weight/height that was reported weight/height, not measured, from various sources (31, 40, 42, 44, 47), did not fully describe their methods for assessing all outcomes (10, 13, 17, 20, 24, 35, 49), or used unstandardized methods (2, 37, 38).

Several authors of the RCTs noted limitations regarding insufficient sample size/power and/or did not assess the impact of high loss to follow-up (2, 3, 6, 13, 16–18). Most of the observational studies had adequate sample sizes to investigate the relationship between types and/or amounts of CFB and outcomes although 15 (of 30) did not account for missing data/high attrition rates. Adequacy of statistical methods in several of the RCTs was insufficient due to a lack of detail describing data in analyses or figures (9, 17, 19, 27, 46). Adequacy of statistical methods in several of the observational studies could not be determined due to insufficient description and/or lack of statistical correction for multiple comparisons (32, 33, 35, 44, 49). In many of the RCTs, blinding of investigators could not be determined and participants were not blinded due to receipt of specific types and/or amounts of CFB. Blinding of outcome assessors could not be determined in the majority of the observational studies

### Research recommendations

In order to better understand the relationship between types and/or amounts of CFB and growth, size, body composition, and/or risk of overweight or obesity, future research should consider:

- Rigorous study designs that directly examine the effects of specific types and amounts of CFB such as fruits, vegetables, meat, cereal, oil sources of fat/fatty acids, and dairy products on multiple growth-related outcomes over longer duration of intervention and follow-up.
- Evidence examining foods that may be historically non-traditional complementary foods in settings such as the U.S. (e.g., legumes, nuts and seeds).
- Additional observational evidence regarding consumption of CFB that are not nutrient-dense (e.g., contain added sugars, refined starches, or solid fats) during the CF period, which may influence energy balance, growth, and development
- Sufficient breadth and depth of duration of follow-up to determine short- and long-term influences of CFB on growth, size, and body composition (i.e., multiple studies that examine the relationship between types and amounts of CFB consumed and outcomes shortly after the CF period as well as into childhood, adolescence, and adulthood).
- Consistency across research investigating dietary patterns during the CF period, with respect to labeling dietary patterns (avoiding judgements about “adequacy”), analytical methods used to derive and assign patterns, foods and food groupings included; and documentation of human milk and/or formula intake.

Additional adjustments in observational studies to the extent possible for confounding factors, including: parental education, socioeconomic status, child sex, maternal age, race/ethnicity, feeding practices including dietary intake/patterns between baseline and follow-up, birth size, gestational age, baseline growth status.

### Included articles

1 Davidsson, L, Mackenzie, J, Kastenmayer, P, . Dietary fiber in weaning cereals: a study of the effect on stool characteristics and absorption of energy, nitrogen, and minerals in healthy infants. Journal of pediatric gastroenterology and nutrition. 1996;22(2):167–79.8642490
2 Dube, K, Schwartz, J, Mueller, M J, . Complementary food with low (8%) or high (12%) meat content as source of dietary iron: a double-blinded randomized controlled trial. European journal of nutrition. 2010;49(1):11–8.19618230
3 Engelmann, M D, Sandstrom, B, Michaelsen, K F. Meat intake and iron status in late infancy: an intervention study. Journal of pediatric gastroenterology and nutrition. 1998;26(1):26–33.9443116
4 Hoffman, D R, Theuer, R C, Castaneda, Y S, . Maturation of visual acuity is accelerated in breast-fed term infants fed baby food containing DHA-enriched egg yolk. The Journal of nutrition. 2004;134(9):2307–13.15333721
5 Krebs, N F, Westcott, J E, Butler, N, . Meat as a first complementary food for breastfed infants: feasibility and impact on zinc intake and status. Journal of pediatric gastroenterology and nutrition. 2006;42(2):207–14.16456417
6 Libuda, L, Mesch, C M, Stimming, M, . Fatty acid supply with complementary foods and LC-PUFA status in healthy infants: results of a randomised controlled trial. European journal of nutrition. 2015.
7 Lind T, Persson L, Lonnerdal B, Stenlund H, Hernell O. Effects of weaning cereals with different phytate content on growth, development and morbidity: a randomized intervention trial in infants from 6 to 12 months of age. Acta paediatrica (Oslo, Norway : 1992). 2004;93(12):1575–82.
8 Liu, D S, Bates, C J, Yin, T A, . Nutritional efficacy of a fortified weaning rusk in a rural area near Beijing. The American journal of clinical nutrition. 1993;57(4):506–11.8460605
9 Lonnerdal, B, Chen, C L. Effects of formula protein level and ratio on infant growth, plasma amino acids and serum trace elements. II. Follow-up formula. Acta paediatrica Scandinavica. 1990;79(3):266–73.2333740
10 Makrides, M, Hawkes, J S, Neumann, M A, . Nutritional effect of including egg yolk in the weaning diet of breast-fed and formula-fed infants: a randomized controlled trial. The American journal of clinical nutrition. 2002;75(6):1084–92.12036817
11 Makrides, M, Leeson, R, Gibson, Rap, . A randomized controlled clinical trial of increased dietary iron in breast-fed infants. The Journal of pediatrics. 1998;133(4):559–62.9787699
12 Olaya, G A, Lawson, M, Fewtrell, M S. Efficacy and safety of new complementary feeding guidelines with an emphasis on red meat consumption: a randomized trial in Bogota, Colombia. The American journal of clinical nutrition. 2013;98(4):983–93.23945724
13 Schwartz, J, Dube, K, Sichert H, W, . Modification of dietary polyunsaturated fatty acids via complementary food enhances n-3 long-chain polyunsaturated fatty acid synthesis in healthy infants: a double blinded randomised controlled trial. Archives of disease in childhood. 2009;94(11):876–82.19193660
14 Tang, M, Krebs, N F. High protein intake from meat as complementary food increases growth but not adiposity in breastfed infants: a randomized trial. The American journal of clinical nutrition. 2014;100(5):1322–8.25332329
15 Tang, M, Sheng, X Y, Krebs, N F, . Meat as complementary food for older breastfed infants and toddlers: a randomized, controlled trial in rural China. Food and nutrition bulletin. 2014;35(4 Suppl):S188–92.25639137
16 Virtanen MA, Svahn CJ, Viinikka LU, Raiha NC, Siimes MA, Axelsson IE. Iron-fortified and unfortified cow’s milk: effects on iron intakes and iron status in young children. Acta paediatrica (Oslo, Norway : 1992). 2001;90(7):724–31.
17 Walter, T, Dallman, P R, Pizarro, F, . Effectiveness of iron-fortified infant cereal in prevention of iron deficiency anemia. Pediatrics. 1993;91(5):976–82.8474819
18 Yeung, G S, Zlotkin, S H. Efficacy of meat and iron-fortified commercial cereal to prevent iron depletion in cow milk-fed infants 6 to 12 months of age: a randomized controlled trial. Canadian journal of public health = Revue canadienne de sante publique. 2000;91(4):263–7.10986782
19 de Silva, D G, Rajindrajith, S, Pathmeswaran, A, . An intervention study to monitor weight gain in infants using a home based complementary food recipe and a hand blender. The Ceylon medical journal. 2007;52(3):79–83.18020022
20 Abraham, E C, Godwin, J, Sherriff, A, . Infant feeding in relation to eating patterns in the second year of life and weight status in the fourth year. Public health nutrition. 2012;15(9):1705–14.22626031
21 Almquist T, G, Dahlgren, J, Roswall, J, . Milk cereal drink increases BMI risk at 12 and 18 months, but formula does not. Acta paediatrica (Oslo, Norway : 1992). 2013;102(12):1174–9.
22 Ay, L, Hokken K, A C, Mook K, D O, . Tracking and determinants of subcutaneous fat mass in early childhood: the Generation R Study. International journal of obesity (2005). 2008;32(7):1050–9.18560371
23 Baird, J, Poole, J, Robinson, S, . Milk feeding and dietary patterns predict weight and fat gains in infancy. Paediatric and perinatal epidemiology. 2008;22(6):575–86.19000296
24 Barton, S J, Howard, P K, Rayens, M K. The effects of infant feeding decisions on infant growth. Journal for specialists in pediatric nursing : JSPN. 2002;7(2):64–70.12061494
25 Bell, L K, Golley, R K, Daniels, L, . Dietary patterns of Australian children aged 14 and 24 months, and associations with socio-demographic factors and adiposity. European journal of clinical nutrition. 2013;67(6):638–45.23443830
26 Cantoral, A, Tellez R, M M, Ettinger, A S, . Early introduction and cumulative consumption of sugar-sweetened beverages during the pre-school period and risk of obesity at 8-14 years of age. Pediatric obesity. 2016;11(1):68–74.25891908
27 Carruth BR, Skinner JD, Houck KS, Moran JD. Addition of supplementary foods and infant growth (2 to 24 months). Journal of the American College of Nutrition. 2000;19:405–12.10872903
28 Dagnelie, P C, van S, W A. Macrobiotic nutrition and child health: results of a population-based, mixed-longitudinal cohort study in The Netherlands. The American journal of clinical nutrition. 1994;59(5 Suppl):1187s–96s.8172122
29 Durmus, B, Heppe, D H, Gishti, O, . General and abdominal fat outcomes in school-age children associated with infant breastfeeding patterns. The American journal of clinical nutrition. 2014;99(6):1351–8.24622802
30 Durmus B, Ay L, Duijts L, Moll HA, Hokken-Koelega AC, Raat H, . Infant diet and subcutaneous fat mass in early childhood: the Generation R Study. European journal of clinical nutrition. 2012;66:253–60.21989323
31 Gaffney, K F, Kitsantas, P, Cheema, J. Clinical practice guidelines for feeding behaviors and weight-for-age at 12 months: a secondary analysis of the Infant Feeding Practices Study II. Worldviews on evidence-based nursing / Sigma Theta Tau International, Honor Society of Nursing. 2012;9(4):234–42.
32 Garden, F L, Marks, G B, Simpson, J M, . Body mass index (BMI) trajectories from birth to 11.5 years: relation to early life food intake. Nutrients. 2012;4(10):1382–98.23201761
33 Garden FL, Marks GB, Almqvist C, Simpson JM, Webb KL. Infant and early childhood dietary predictors of overweight at age 8 years in the CAPS population. European journal of clinical nutrition. 2011;65(4):454–62.21346718
34 Golley, R K, Smithers, L G, Mittinty, M N, . Diet quality of U.K. infants is associated with dietary, adiposity, cardiovascular, and cognitive outcomes measured at 7-8 years of age. The Journal of nutrition. 2013;143(10):1611–7.23946339
35 Hertrampf, E, Olivares, M, Pizarro, F, . Haemoglobin fortified cereal: a source of available iron to breast-fed infants. European journal of clinical nutrition. 1990;44(11):793–8.2086208
36 Iannotti, L L, Zavaleta, N, Leon, Z, . Growth and body composition of Peruvian infants in a periurban setting. Food and nutrition bulletin. 2009;30(3):245–53.19927604
37 Kalies, H, Heinrich, J, Borte, N, . The effect of breastfeeding on weight gain in infants: results of a birth cohort study. European journal of medical research. 2005;10(1):36–42.15737952
38 Kramer, M S, Guo, T, Platt, R W, . Feeding effects on growth during infancy. The Journal of pediatrics. 2004;145(5):600–5.15520757
39 Morgan, J, Taylor, A, Fewtrell, M. Meat consumption is positively associated with psychomotor outcome in children up to 24 months of age. Journal of pediatric gastroenterology and nutrition. 2004;39(5):493–8.15572888
40 Pan L, Li R, Park S, Galuska DA, Sherry B, Freedman DS. A longitudinal analysis of sugar-sweetened beverage intake in infancy and obesity at 6 years. Pediatrics. 2014;134 Suppl 1:S29–35.25183752
41 Robinson SM, Marriott LD, Crozier SR, Harvey NC, Gale CR, Inskip HM, . Variations in infant feeding practice are associated with body composition in childhood: a prospective cohort study. The Journal of clinical endocrinology and metabolism. 2009;94:2799–805.19435826
42 Rose, C M, Savage, J S, Birch, L L. Patterns of early dietary exposures have implications for maternal and child weight outcomes. Obesity (Silver Spring, Md). 2016;24(2):430–8.
43 Santorelli, G, Fairley, L, Petherick, E S, . Ethnic differences in infant feeding practices and their relationship with BMI at 3 years of age - results from the Born in Bradford birth cohort study. The British journal of nutrition. 2014;111(10):1891–7.24513174
44 Schack-Nielsen L, Sorensen T, Mortensen EL, Michaelsen KF. Late introduction of complementary feeding, rather than duration of breastfeeding, may protect against adult overweight. The American journal of clinical nutrition. 2010;91:619–27.20032492
45 Sonneville, K R, Long, M W, Rifas S, S L, . Juice and water intake in infancy and later beverage intake and adiposity: could juice be a gateway drink? Obesity (Silver Spring, Md). 2015;23(1):170–6.
46 Tantracheewathorn, S. Growth of breast-fed and formula-fed infants compared with national growth references of Thai children. Journal of the Medical Association of Thailand = Chotmaihet thangphaet. 2005;88(2):168–75.15962666
47 Wen, X, Kong, K L, Eiden, R D, . Sociodemographic differences and infant dietary patterns. Pediatrics. 2014;134(5):e1387–98.25311608
48 Wosje, K S, Specker, B L, Giddens, J. No differences in growth or body composition from age 12 to 24 months between toddlers consuming 2% milk and toddlers consuming whole milk. Journal of the American Dietetic Association. 2001;101(1):53–6.11209585
49 Zheng, J S, Liu, H, Zhao, Y M, . Complementary feeding and childhood adiposity in preschool-aged children in a large Chinese cohort. The Journal of pediatrics. 2015;166(2):326–31.e2.25491091

### Other references

50 United Nations Development Programme. Human Development Report 2014. Sustaining Human Progress: Reducing Vulnerabilities and Building Resilience. New York; 2014.
51 World Bank. The Little Data Book 2016 Washington, DC 2016 [Available from: https://openknowledge.worldbank.org/handle/10986/23968.

## ANALYTIC FRAMEWORK

The analytic framework illustrates the overall scope of the review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. This is the analytic framework for the systematic reviews conducted to examine the relationship between complementary feeding and growth, size, and body composition.

Figure 1 Analytic framework

This is the analytic framework for the systematic review questions about complementary feeding and growth, size, and body composition. For this systematic review, the target population considered was generally health infants fed human milk, infant formula, or both. The interventions or exposures considered were types and amounts consumed of complementary foods and beverages and their comparators were different types and amounts. The outcomes considered were growth, size, and/or body composition. This included a range of health outcomes such as weight and length/height, BMI, BMI percentile or z-score, waist circumference, weight or weight status change, weight- and length-for-age, fat mass, fat-free mass, skinfold thickness, incidence/prevalence of weight status (i.e., underweight, healthy weight, overweight, obesity) or malnutrition indicators (failure to thrive, stunting, wasting). The key confounders were education, socioeconomic status, sex, race/ethnicity, maternal age, milk feeding practices, birth size, and gestational age.

## SEARCH PLAN AND RESULTS

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review question(s) on the types and amounts of CFB consumed and growth, size, and body composition. The inclusion and exclusion criteria are a set of characteristics to determine which studies will be included or excluded in the systematic review.

Table 7 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials; - Prospective cohort studies; - Retrospective cohort studies; - Case-control studies; - Pre/post studies with a control | - Cross-sectional studies; - Uncontrolled studies; - Pre/post studies without a control; - Narrative reviews; - Systematic reviews; - Meta-analyses
Independent variable (intervention or exposure) | Types and amounts of complementary foods and beverages (CFB) consumed. CFB are foods and beverages other than human milk or infant formula (liquids, semisolids, and solids) provided to an infant or young child to provide nutrients and energy. | Isolated consumption of human milk, infant formulas (e.g., milk-based, soy, partially-hydrolyzed, extensive-hydrolyzed, amino acid-based), fluid cow’s milk before 12 months of age, or vitamin and mineral supplements (e.g., iron drops)
Comparator | Different types and amounts of CFB | N/A
Dependent variables (outcomes) | - Weight and length/height; - BMI, BMI percentile for age and z-score; - Waist circumference; - Weight change; - Weight status change; - Weight-for-age, length/stature-for-age, weight-for-length, head, arm, and thigh circumference for age; - Change across more than one time point of weight-for age, length-for-age, weight-for-length, head, arm, and thigh circumference for age; - % fat mass, % fat free mass; - Skinfold thickness; - Incidence of healthy weight, overweight, obesity; - Incidence of underweight or failure to thrive, stunting, and wasting in infants and children | N/A
Date range | - January 1980 - July 2016
Language | - Studies published in English | - Studies published in languages other than English
Publication status | - Studies published in peer-reviewed journals | - Grey literature, including unpublished data, manuscripts, reports, abstracts, conference proceedings
Country ^1^ | - Studies conducted in Very High or High Human Development Countries | - Studies conducted in Medium or Low Human Development Countries
Study participants | - Human subjects; - Males; - Females | - Hospitalized patients, not including birth and immediate post-partum hospitalization of healthy babies
Age of study participants | - Age at intervention or exposure:; ○ Infants (0-12 months); ○ Toddlers (12-24 months); - Age at outcome:; ○ Infants (0-12 months); ○ Toddlers (12-24 months); ○ Child (2-5 years); ○ Child (6-12 years); ○ Adolescents (13-18 years); ○ Adults (19 and older); ○ Older adults (65 to 79 years); ○ Older adults (80+ years) | - Age at intervention or exposure:; ○ Child (2-5 years); ○ Child (6-12 years); ○ Adolescents (13-18 years); ○ Adults (19 and older); ○ Older adults (65 to 79 years); ○ Older adults (80+ years)
Health status of study participants | - Studies done in generally healthy populations; - Studies done in populations where infants were full term (≥37 weeks gestational age); - Studies done in populations with elevated chronic disease risk, or that enroll some participants with a disease or with the health outcome of interest | - Studies that exclusively enroll subjects with a disease or with the health outcome of interest; - Studies done in hospitalized or malnourished subjects; - Studies of exclusively pre-term babies (gestational age <37 weeks) or babies that are small for gestational age (<2500g); - Studies of subjects with infectious diseases (e.g. HIV/AIDS) (or with mothers diagnosed with an infectious disease)

1 The ratings of country development (e.g., high, medium, low, very low) were based on the Human Development Report 2014 (50). When a country was not included in the Human Development Report 2014 ranking, country classification from the World Bank was used instead (51). Medium Development countries were originally included, but due to concerns about generalizability to the U.S. of study participants (i.e., baseline health status) and complementary foods and beverages typically consumed, a decision was made to exclude “Medium” countries in October 2017

### Search terms and electronic databases used

#### PubMed

Date(s) Searched: 7/19/2016

Search Terms:

Final:

Complementary OR supplementary OR wean* OR transition* OR introduc* OR “Infant Nutritional Physiological Phenomena”[Mesh:noexp] OR weaning[mesh] OR ((bottle*) NOT (milk OR formula))

AND (feeding* OR food OR beverage*[tiab] OR beverages[mh] OR eating OR diet[tiab] OR diet[mh] OR meal*[tiab] OR meals[mh] OR “Food and Beverages”[Mesh] OR diets[tiab] OR cereal*[tiab] OR “Edible Grain”[Mesh] OR bread*[tiab] OR whole grain* OR juice*[tiab] OR milk[tiab] OR “Milk”[Mesh] OR dairy[tiab] OR “Dairy Products”[Mesh] OR meat[tiab] OR cheese[tiab] OR yogurt[tiab] OR yoghurt*[tiab] OR fruit*[tiab] OR “Fruit”[Mesh] OR vegetable*[tiab] OR “Vegetables”[Mesh] OR egg*[tiab] OR “Eggs”[Mesh] OR nut[tiab] OR nuts[tiab] OR peas[tiab] OR beans[tiab] OR legume*[tiab] OR snack*[tiab] OR bread[mh] OR honey[mh] OR vegetable*[tiab] OR “Vegetables”[Mesh] OR egg*[tiab] OR “Eggs”[Mesh:noexp] OR “egg white”[mh] OR “egg yolk”[mh] OR snack*[tiab] OR candy[mh] OR “Fast Foods”[Mesh] OR meat[mh] OR molasses[mh] OR nuts[mh] OR “Raw Foods”[Mesh] OR seeds[mh])

OR “infant food”[mesh]

OR infant feed*

OR

(breast feeding[mh] OR breastfeeding[tiab] OR breast feeding*[tiab] OR breast-feeding*[tiab] OR breastfed[tiab] OR breast-fed[tiab] OR breast-feed OR breast-feeds)

OR

(Bottle feeding[mh] OR bottle feeding*[tiab]s OR bottle feeding OR bottle-feeding*[tiab] OR bottle-feedings OR bottle-fed[tiab] OR “bottle fed”[tiab])

NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic[sb])

OR ((Solid food*) OR solids));

AND

Growth[mh:noexp] OR “Child Development”[Mesh] OR “Growth Charts”[Mesh] OR “growth and development” [Subheading] OR “growth and development”[tiab] OR “Growth and Development”[Mesh:noexp] OR “Growth”[tiab] OR development*[tiab] OR “Child Development”[Mesh] OR child develop*[tiab] OR tooth[mh] OR tooth[tiab] OR teeth[tiab] OR movement[mh] OR “Overnutrition”[Mesh] OR under-nutrition[tiab] OR undernutrition[tiab] OR “developmental delay”[tiab] OR “Motor Skills”[Mesh] OR “Nonverbal Communication”[Mesh]

Standing[tiab] OR sitting[tiab] OR walking[tiab] OR crawling[tiab] OR “Motor Skills”[Mesh] OR Ages and Stages Questionnaire* OR ASQ[tiab]

OR Cognitive[tiab] OR cognition[mh] OR cognition OR learning OR “Learning Disorders”[Mesh] OR “Intellectual Disability”[Mesh] OR intelligence[tiab] OR intelligence[mh] OR “Achievement”[Mesh] OR “Aptitude”[Mesh] OR “Executive Function”[Mesh] OR memory OR inhibitory control*[tiab] OR “problem solving”[tiab] OR“Social-emotional development”[tiab] OR “Neurological development”[tiab] OR “mental development”[tiab] OR

“Motor development”[tiab] OR anxiety[tiab] OR anxiety[mh:noexp] OR “Anxiety, Separation”[Mesh] OR depression[tiab] OR depression[mh] OR “Depression, Postpartum”[Mesh] OR “Depressive Disorder”[Mesh] OR

“Visual Acuity”[Mesh] OR “Auditory Perception”[Mesh] OR “Psychological Tests”[Mesh]

OR

(“Bone Density”[Mesh] OR “bone density”[tiab] OR “Bone Development”[Mesh] OR “Bone Development”[tiab] OR “Fractures, Bone”[Mesh] OR “Bone Diseases”[Mesh] OR osteoporosis[tiab] OR (bone[tiab] AND fracture*[tiab]) OR “Rickets”[Mesh] OR ricket*[tiab] OR bone mineral*[tiab] OR “bone mass”[tiab] OR bone health*[tiab] OR “Bone Demineralization, Pathologic”[Mesh] OR bone demineral*[tiab])

OR

(“body size”[tiab] OR body size[mh] OR obesity[tiab] OR obese[tiab] OR overweight[mh] OR obesity[mh] OR overweight [tiab] OR adipos*[tiab] OR adiposity[mh] OR “body composition”[mh] OR body fat distribution[mh] OR “body fat”[tiab] OR “body weight”[tiab] OR body weight[mh] OR birth weight*[tiab] OR weight gain[mh] OR weight loss[mh] OR “body-weight”[tiab] OR “weight gain”[tiab] OR weight-gain[tiab] OR weight loss[tiab] OR weight-loss[tiab] OR “Body Weights and Measures”[mh] OR weight[ti] OR “Anthropometry”[Mesh:noexp] OR body mass index[mh] OR “body mass index”[tiab] OR BMI[tiab] OR “weight status”[tiab] OR “adipose tissue”[mh] OR “healthy weight”[tiab] OR waist circumference[mh] OR “body mass”[ti] OR “fat mass”[tiab] OR body weight changes[mh] OR “waist circumference”[tiab] OR ideal body weight[mh] OR waist-hip ratio[mh] OR Waist Hip*[tiab] OR body height*[tiab] OR Crown-Rump Length*[tiab] OR head circumference*[tiab] OR arm circumference*[tiab] OR thigh circumference* OR limb circumference* OR fat free mass*[tiab] OR skinfold[tiab] OR skin fold*[tiab])

AND

infant* OR baby OR babies OR toddler* OR newborn*[tiab] OR “Child, Preschool”[Mesh] OR preschool*[tiab] OR pre-school*[tiab] OR “early childhood”[tiab] OR “early years”[tiab] OR pre-k[tiab] OR pre-primary[tiab] OR under five*[ti] OR young child*[ti] OR “head start”[tiab] OR prekindergarten[tiab] OR pre-kindergarten[tiab] OR weanling*

OR limit to child, preschool

for child 0-18 all develop outcomes

for all; body wgt/comp/bone

NOT

nutritional status[mh] OR nutritional status*[tiab] OR Nutrition Status*[tiab] OR Iron[mh] OR iron[tiab] OR “Anemia”[Mesh] OR “Anemia”[tiab] OR iron deficien*[tiab] OR ferritin*[tiab] OR ferrous[tiab] OR “Transferrin”[Mesh] OR “Transferrin”[tiab] OR zinc OR “Vitamin D”[Mesh] OR “Vitamin D”[tiab] OR “Vitamin D Deficiency”[Mesh] OR “Vitamin B 12”[Mesh] OR “Vitamin B 12”[tiab] OR “Vitamin B12”[tiab] OR “Vitamin B 12 Deficiency”[Mesh] OR Cobamide*[tiab] OR Cobalamin*[tiab] OR Cyanocobalamin[tiab] OR Folate[tiab] OR “Folic Acid”[Mesh] OR folacin[tiab] OR vitamin b9*[tiab] OR Fatty acid*[tiab] OR “Fatty Acids”[Mesh:noexp] OR fatty acid*[tiab] OR “Fatty Acids, Unsaturated”[Mesh:noexp] OR Arachidonic acid*[tiab] OR linolenic acid*[tiab] OR linoleic acid*[tiab] OR Docosahexaenoic Acid*[tiab] OR Eicosapentaenoic Acid*[tiab] OR gamma-Linolenic Acid*[tiab] OR “Arachidonic Acids”[Mesh] OR “Fatty Acids, Essential”[Mesh] OR “Fatty Acids, Omega-3”[Mesh] OR “Fatty Acids, Omega-6”[Mesh] OR alpha-Linolenic Acid*[tiab] OR “Fatty Acids, Essential”[Mesh] OR “Linolenic Acids”[Mesh] OR “Trans Fatty Acids”[Mesh] OR “Fatty Acids, Monounsaturated”[Mesh]

for nonmedline[sb]: NOT animals by: NOT (sheep[ti] OR lamb[ti] OR lambs[ti] OR calving[ti] OR calves[ti] OR mice[ti] OR mouse[ti] OR pigs[ti] OR cows[ti] OR piglets[ti] OR cow[ti] OR piglet[ti] OR monkey[ti] OR rats[ti] OR rat[ti] OR animal*[ti])

#### Embase

Date(s) Searched: 8/1/16

Search Terms:

(Complementary OR supplementa* OR wean* OR transition* OR introduc* OR family) NEAR/3 (feed* OR food* OR beverage* OR eating OR diet)

OR

(Complementary OR transition* OR introduct* OR wean*) AND (food/exp OR ‘baby food’/exp OR ‘cereal’/exp OR ‘dairy product’/exp OR ‘egg’/exp OR ‘fruit’/exp OR ‘meat’/exp OR ‘sea food’/exp OR ‘milk’/exp OR fish/exp OR ‘poultry’/exp OR ‘beverage’/exp OR ‘vegetable’/exp OR nut/exp OR pea/exp OR meal/exp)

OR

(Complementary OR supplementa* OR wean* OR transition* OR introduc*) NEAR/5 (‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR beverage* OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR bread* OR yog*urt* OR cheese* OR juice* OR rice OR soup OR legume* OR snack* OR meal*) (for Embase)

OR ‘baby food’/de OR (solid NEAR/2 food*):ab,ti

AND

(infant*:ti,ab OR infant/exp) OR (baby OR babies OR toddler* OR newborn* OR nurser*):ti,ab OR ‘newborn’/exp OR ‘newborn care’/exp OR preschool*:ti,ab OR pre-school:ti,ab OR ‘preschool child’/exp OR ‘infancy’/exp OR “early childhood”:ti,ab OR “early years” OR pre-k:ti,ab OR ‘nursery’/exp OR ‘nursery school’/exp OR prekindergarten:ti,ab OR pre-kindergarten:ti,ab OR weanling*

AND ([in process]/lim OR [article]/lim OR [article in press]/lim) AND ([embase]/lim NOT [medline]/lim)

AND

Limit to humans:

AND

‘executive function’/exp OR ‘executive function’:ti,ab OR ‘learning’/exp OR ‘intelligence’/exp OR ‘mental development’/exp OR ‘mental development’:ti,ab OR intelligence:ti,ab OR cogniti*:ti,ab OR ‘cognition’/exp OR ‘cognition assessment’/exp OR aptitude:ti,ab OR ‘memory’/exp OR memory:ti,ab OR ‘anxiety’/exp OR ‘anxiety’:ti,ab OR ‘depression’/exp OR depressi*:ti,ab OR ‘visual acuity’/exp OR visual:ti OR ‘hearing’/exp OR hearing:ti,ab OR auditory:ti,ab OR ‘postnatal development’/exp OR ‘postnatal development’:ti,ab OR ‘overnutrition’/exp OR ‘overnutrition’:ti,ab OR undernutrition:ti,ab OR “developmental delay”:ti,ab OR ‘nonverbal communication’/exp

OR

(‘metabolic bone disease’/exp OR osteoporosis:ti,ab OR (bone NEAR/2 (disease* OR fracture* OR injur* OR health* OR density OR mineralize* OR demineraliz*)):ti,ab OR ricket*:ti,ab OR ‘bone injury’/exp OR ‘bone density’/exp)

AND

‘body size’/de OR ‘body size’:ti,ab OR ‘obesity’/exp OR overweight:ab,ti OR ‘macrosomia’/exp OR obese:ab,ti OR obesity:ab,ti OR ‘weight gain’:ab,ti OR adiposity:ab,ti OR adipose:ab,ti OR ‘body weight’/exp OR ‘body weight’:ti,ab OR ‘weight gain’/de OR ‘body composition’/exp OR ‘body composition’:ti,ab OR ‘body fat’:ab,ti OR ‘anthropometry’/de OR ‘body mass’/de OR bmi:ab,ti OR ‘body mass’:ab,ti OR weight:ab,ti OR (waist NEXT/1 hip NEXT/1 ratio*) OR ‘body fat’/de OR ‘adipose tissue’/exp OR skinfold OR ‘skin fold’:ti,ab OR ‘fat mass’:ti,ab OR ‘fat mass’/exp OR ‘anthropometric parameters’/exp OR circumference OR length OR height

OR

‘body growth’/exp ‘body growth’:ti,ab OR ‘growth rate and growth regulation’/exp OR ‘postnatal growth’/exp OR ‘human development’/exp OR ‘Bayley Scales of Infant Development’/exp OR ‘cognition assessment’/exp OR ‘mental function assessment’/de

#### Cochrane

Date(s) Searched: 8/9/16

Search Terms:

(feed* OR food* OR beverage*OR diet* OR ‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR beans OR legume* OR nut OR cereal OR beverage* OR bread* OR seafood OR yog*urt* OR cheese OR juice OR snack OR yogurt OR yoghurt OR nut OR nuts OR honey OR meal OR meals) NEAR/3 (Complementary OR supplementa* OR wean* OR transition* OR introduct* OR family)

OR

[mh ^“Infant Nutritional Physiological Phenomena”] OR [mh weaning] OR ((bottle*) NOT (milk OR formula))

AND ([mh beverages] OR [mh eating] OR [mh diet] OR [mh meals] OR [mh “Food and Beverages”] OR [mh “Edible Grain”] OR [mh “Milk”] OR dairy[:ti,ab OR [mh “Dairy Products”] OR [mh “Fruit”] OR [mh “Vegetables”] OR [mh “Eggs”] OR [mh bread] OR [mh honey] OR [mh “Vegetables”] OR [mh ^“Eggs”] OR [mh “egg white”] OR [mh “egg yolk”] OR [mh candy] OR [mh “Fast Foods”] OR [mh meat] OR [mh molasses] OR [mh nuts] OR [mh “Raw Foods”] OR [mh seeds])

OR

((Infant* OR baby* OR babies) NEAR/2 food*):ti,ab OR [mh “infant food”]

AND

[mh ^Growth] OR [mh “Child Development”] OR [mh “Growth Charts”] OR “growth and development” OR [mh ^“Growth and Development”] OR [mh “Child Development”] OR (child NEAR/1 develop*):ti,ab OR [mh tooth] OR tooth:ti,ab OR teeth:ti,ab OR [mh movement] OR [mh “Overnutrition”] OR “under-nutrition:ti,ab OR undernutrition:ti,ab OR [mh “Motor Skills”] OR [mh “Nonverbal Communication”]

OR

‘body growth’:ti,ab OR ‘growth rate and growth regulation’ OR ‘postnatal growth’:ti,ab OR ‘human development’:ti,ab OR ‘Bayley Scales of Infant Development’

OR Standing:ti,ab OR sitting:ti,ab OR walking:ti,ab OR crawling:ti,ab OR “Ages and Stages Questionnaire” OR ASQ:ti,ab

OR [mh cognition] OR [mh learning] OR [mh “Learning Disorders”] OR [mh “Intellectual Disability”] OR intelligence:ti,ab OR [mh intelligence] OR [mh “Achievement”] OR [mh “Aptitude”] OR [mh “Executive Function”] OR (inhibitory NEAR/1 control*):ti,ab OR “problem solving”:ti,ab OR “Social-emotional development”:ti,ab OR “Neurological development”:ti,ab OR “mental development”:ti,ab OR “Motor development”ti,ab OR [mh ^anxiety] OR [mh “Anxiety, Separation”] OR [mh depression] OR [mh “Depression, Postpartum”] OR [mh “Depressive Disorder”] OR [mh “Visual Acuity”] OR [mh “Auditory Perception”] OR [mh “Psychological Tests”]

OR Stunt*:ti,ab OR wasting:ti,ab

OR

cogniti*:ti,ab OR aptitude:ti,ab OR memory:ti,ab OR [mh memory] OR ‘anxiety’:ti,ab OR depressi*:ti,ab OR visual:ti,ab OR vision:ti,ab OR hearing:ti,ab OR auditory:ti,ab OR ‘postnatal development’:ti,ab OR ‘overnutrition’:ti,ab OR “developmental delay”:ti,ab OR ‘nonverbal communication’

OR

[mh “Bone Density”] OR [mh “Bone Development”] OR [mh “Fractures, Bone”] OR [mh “Bone Diseases”] OR [mh “Rickets”] OR [mh “Bone Demineralization, Pathologic”] OR osteoporosis:ti,ab OR (bone NEAR/2 (disease* OR fracture* OR injur* OR health* OR density OR mineral* OR demineral* OR develop* OR mass)):ti,ab OR ricket*:ti,ab

OR

‘body size’:ti,ab OR overweight:ab,ti OR ‘macrosomia’:ti,ab OR obese:ab,ti OR obesity:ab,ti OR adipos*:ab,ti OR ‘body weight’:ti,ab OR ‘weight gain’:ti,ab OR ‘body composition’:ti,ab OR ‘body fat’:ab,ti OR ‘anthropometr*’:ti,ab OR bmi:ab,ti OR ‘body mass’:ab,ti OR (waist NEXT/1 hip NEXT/1 ratio*) OR ‘body fat’:ti,ab OR ‘adipose tissue’:ti,ab OR skinfold:ti,ab OR ‘skin fold’:ti,ab OR ‘fat mass’:ti,ab OR circumference:ti,ab OR length:ti,ab OR height:ti,ab

([mh “body size”] OR [mh overweight] OR [mh obesity] OR [mh adiposity] OR [mh “body composition”] OR [mh “body fat distribution”] OR [mh “body weight”] OR [mh “weight gain”] OR [mh “weight loss”] OR “weight gain”:ti,ab OR “weight loss”:ti,ab OR “weight-loss”:ti,ab OR [mh “Body Weights and Measures”] OR weight:ti OR [mh ^“Anthropometry”] OR [mh “body mass index”] OR “weight status”:ti,ab OR [mh “adipose tissue”] OR “healthy weight”:ti,ab OR [mh “waist circumference”] OR [mh “body weight changes”] OR [mh “ideal body weight”] OR [mh “waist-hip ratio”] OR “Waist Hip”:ti,ab OR “waist-hip”:ti,ab OR “Crown-Rump”:ti,ab OR “fat free mass”:ti,ab)

NOT (pubmed OR embase)

#### CINAHL

Date(s) Searched: 8/22/2016

Search Terms:

(MH “Food and Beverages+”) OR (MH “Food”) OR (MH “Diet”) OR (MH “Eating”) OR (MH “Eating Behavior”) OR (MH “Taste”) OR (MH “Taste Buds”) OR (MH “Cereals”) OR (MH “Dairy Products”) OR (MH “Yogurt”) OR (MH “Cheese”) OR (MH “Milk”) OR (MH “Eggs”) OR (MH “Fruit”) OR (MH “Fruit Juices”) OR (MH “Meat”) OR (MH “Seafood”) OR (MH “Fish”) OR (MH “Poultry”) OR (MH “Vegetables”) OR (MH “Nuts”) OR (MH “Legumes”) OR (MH “Bread”) AND (Complementary OR supplementa* OR wean* OR transition* OR introduc*)

OR

(‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR beverage* OR bread* OR seafood OR yog*urt* OR cheese* OR juice*) N5 (Complementary OR supplementa* OR wean* OR transition* OR introduc* OR family)

OR (Infant* OR baby OR babies) N2 food*

NOT

(MH “Nutritional Status”) OR “nutritional status” OR (MH “Nutritional Requirements”) OR (MH “Vitamin D”) OR (MH “Vitamin D Deficiency”) OR (MH “Vitamin B12 Deficiency”) OR (MH “Anemia”) OR “anemia” OR (MH “Anemia, Iron Deficiency”) OR (MH “Iron”) OR (MH “Zinc”) OR (MH “Vitamin B12”) OR (MH “Vitamin B12 Deficiency”) OR (MH “Folic Acid”) OR (MH “Niacin”) OR (MH “Folic Acid Deficiency”) OR “folate” OR “folacin” OR cyanocobalamin* OR cobalamin* OR cobamamide* OR (MH “Fatty Acids”) OR “fatty acids” OR (MH “Fatty Acids, Omega-6”) OR (MH “Fatty Acids, Omega-3”) OR (MH “Fatty Acids, Unsaturated”) OR (MH “Trans Fatty Acids”) OR (MH “Fatty Acids, Monounsaturated”) OR (MH “Fatty Acids, Saturated”) OR (MH “Fatty Acids, Essential”) OR (MH “Arachidonic Acids”) OR (MH “Docosahexaenoic Acids”) OR (MH “Linolenic Acids”) OR (MH “Linoleic Acids”)

AND

osteoporosis OR (bone n2 (disease* OR fracture* OR injur* OR health* OR density OR mineralize* OR demineraliz*)) OR ricket* OR (MH “Osteoporosis”) OR (MH “Bone Density”) OR

(MH “Bone Diseases+”) OR (MH “Bone Diseases, Developmental+”) OR (MH “Rickets+”)

OR

(MH “Executive Function”) OR (MH “Learning+”) OR (MH “Intelligence+”) OR “intelligence” OR (MH “Intelligence Tests”) OR (MH “Cognition+”) OR “cognition” OR “mental development” OR (MH “Aptitude”) OR “aptitude” OR (MH “Aptitude Tests+”) OR (MH “Memory+”) OR “memory” OR (MH “Anxiety+”) OR “anxiety” OR (MH “Depression+”) OR “depression” OR (MH “Visual Acuity”) OR (MH “Visual Perception+”) OR (MH “Hearing+”) OR “auditory” OR “overnutrition” OR “undernutrition” OR (MH “Nonverbal Communication+”) OR “postnatal development” OR OR “developmental delay”

OR

(MH “Anthropometry+”) OR (MH “Body Weights and Measures+”) OR (MH “Body Weight+”) OR

(MH “Bone Development+”) OR (MH “Growth+”) OR (MH “Human Development+”) OR “bayley scales” OR “mental function” OR (MH “Body Size”) OR (MH “Obesity+”) OR “overweight” OR “macrosomia” OR (MH “Weight Gain+”) OR (MH “Waist-Hip Ratio”) OR (MH “Body Composition+”) OR (MH “Adipose Tissue+”) OR (MH “Abdominal Fat”) OR (MH “Fat Free Mass”) OR (MH “Body Mass Index”) OR (MH “Skinfold Thickness”) OR (MH “Head Circumference”) OR (MH “Arm Circumference”) OR (MH “Waist Circumference”) OR (MH “Growth and Development (Omaha)”) OR (MH “Body Height”) OR (MH “Crown-Rump Length”) OR (MH “Leg Length Inequality”) OR (MH “Mean Length of Utterance”)

Figure 2 Flow chart of literature search and screening results

This is a flow chart summarizing the results of literature screeniing, including the total number of articles screened at each level (title, abstract, and full text) and total numder of articles identified via hand search for systematic reviews on complementary feeding and developmental milestones.

This flow chart illustrates the literature search results for articles examining the relationship between complementary feeding and growth, size, and/or body composition. The results of an electronic database search were screened independently by two NESR analysts by reviewing titles, abstracts, and full text articles to determine which articles met the criteria for inclusion. A manual search was done to ascertain articles not identified through the electronic database search. The systematic review on timing of introduction of CFB included 81 articles, and the systematic review on types and amounts of CFB consumed included 49 articles. The literature search was conducted for multiple systematic reviews that addressed complementary feeding and various health outcomes.

### Excluded articles

The table below lists the excluded articles with at least one reason for exclusion, but may not reflect all possible reasons.

Table 8 Excluded articles

| Citation | Rationale^1^
1 | Complementary feeding in the WHO Multicentre Growth Reference Study. Acta Paediatr Suppl.2006;450:27-37. | DV
2 | Weaning and the weaning diet. Report of the Working Group on the Weaning Diet of the Committee on Medical Aspects of Food Policy. Rep Health Soc Subj (Lond).1994;45:1-113. | Design
3 | Aarts, C.,Kylberg, E.,Hofvander, Y.,Gebre-Medhin, M. Growth under privileged conditions of healthy Swedish infants exclusively breastfed from birth to 4-6 months: a longitudinal prospective study based on daily records of feeding. Acta Paediatr.2003;92:145-51. | IV
4 | Abarin, T.,Yan Wu, Y.,Warrington, N.,Lye, S.,Pennell, C.,Briollais, L. The impact of breastfeeding on FTO-related BMI growth trajectories: an application to the Raine pregnancy cohort study. Int J Epidemiol.2012;41:1650-60. | IV
5 | Abou Samra, H.,Stevens, D.,Binkley, T.,Specker, B. Determinants of bone mass and size in 7-year-old former term, late-preterm, and preterm boys. Osteoporos Int.2009;20:1903-10. | Design, IV
6 | Aboud, F. E.,Akhter, S. A cluster-randomized evaluation of a responsive stimulation and feeding intervention in bangladesh. Pediatrics.2011;127:e1191-7. | IV
7 | Aboud, F. E.,Shafique, S.,Akhter, S. A responsive feeding intervention increases children’s self-feeding and maternal responsiveness but not weight gain. J Nutr.2009;139:1738-43. | IV
8 | Adu-Afarwuah, S.,Lartey, A.,Brown, K. H.,Zlotkin, S.,Briend, A.,Dewey, K. G. Randomized comparison of 3 types of micronutrient supplements for home fortification of complementary foods in Ghana: effects on growth and motor development. Am J Clin Nutr.2007;86:412-20. | IV
9 | Agarwal, K. N.,Agarwal, D. K.,Gupta, A.,Bansal, A. K. Relationship of exclusive breast feeding for 6 mo to linear growth up to 18 mo of age. Indian J Pediatr.2013;80:11-5. | Country
10 | Aggarwal, A.,Arora, S.,Patwari, A. K. Breastfeeding among urban women of low-socioeconomic status: factors influencing introduction of supplemental feeds before four months of age. Indian Pediatr.1998;35:269-73. | Design, IV,DV
11 | Agostoni, C.,Fiocchi, A.,Riva, E.,Terracciano, L.,Sarratud, T.,Martelli, A.,Lodi, F.,D’Auria, E.,Zuccotti, G.,Giovannini, M. Growth of infants with IgE-mediated cow’s milk allergy fed different formulas in the complementary feeding period. Pediatr Allergy Immunol.2007;18:599-606. | IV
12 | Agostoni, C.,Grandi, F.,Gianni, M. L.,Silano, M.,Torcoletti, M.,Giovannini, M.,Riva, E. Growth patterns of breast fed and formula fed infants in the first 12 months of life: an Italian study. Arch Dis Child.1999;81:395-9. | IV
13 | Agostoni, C.,Grandi, F.,Scaglioni, S.,Gianni, M. L.,Torcoletti, M.,Radaelli, G.,Fiocchi, A.,Riva, E. Growth pattern of breastfed and nonbreastfed infants with atopic dermatitis in the first year of life. Pediatrics.2000;106:E73. | IV
14 | Agostoni,C.,Marangoni,F.,Lammardo,A. M.,Giovannini,M.,Riva,E.,Galli,C. Breastfeeding duration, milk fat composition and developmental indices at 1 year of life among breastfed infants. Prostaglandins Leukot Essent Fatty Acids.2001;64:105-9. | IV
15 | Agostoni,C.,Zuccotti,G. V.,Radaelli,G.,Besana,R.,Podesta,A.,Sterpa,A.,Rottoli,A.,Riva,E.,Giovannini,M. Docosahexaenoic acid supplementation and time at achievement of gross motor milestones in healthy infants: a randomized, prospective, double-blind, placebo-controlled trial. Am J Clin Nutr.2009;89:64-70. | IV
16 | Allen, L.,Shrimpton, R. The International Research on Infant Supplementation study: implications for programs and further research. J Nutr.2005;135:666s-669s. | Design
17 | Alm,B.,Aberg,N.,Erdes,L.,Mollborg,P.,Pettersson,R.,Norvenius,S. G.,Goksor,E.,Wennergren,G. Early introduction of fish decreases the risk of eczema in infants. Arch Dis Child.2009;94:11-5. | DV
18 | Almqvist,C.,Garden,F.,Xuan,W.,Mihrshahi,S.,Leeder,S. R.,Oddy,W.,Webb,K.,Marks,G. B. Omega-3 and omega-6 fatty acid exposure from early life does not affect atopy and asthma at age 5 years. J Allergy Clin Immunol.2007;119:1438-44. | IV, DV
19 | Alvarez-Uria, G.,Midde, M.,Pakam, R.,Bachu, L.,Naik, P. K. Effect of Formula Feeding and Breastfeeding on Child Growth, Infant Mortality, and HIV Transmission in Children Born to HIV-Infected Pregnant Women Who Received Triple Antiretroviral Therapy in a Resource-Limited Setting: Data from an HIV Cohort Study in India. ISRN Pediatr.2012;2012:763591. | Health statu
20 | Andersen, L. B.,Molgaard, C.,Michaelsen, K. F.,Carlsen, E. M.,Bro, R.,Pipper, C. B. Indicators of dietary patterns in Danish infants at 9 months of age. Food Nutr Res.2015;59:27665. | Design
21 | Andersen,A. D.,Michaelsen,K. F.,Hellgren,L. I.,Trolle,E.,Lauritzen,L. A randomized controlled intervention with fish oil versus sunflower oil from 9 to 18 months of age: exploring changes in growth and skinfold thicknesses. Pediatr Res.2011;70:368-74. | IV
22 | Andersen,L. B.,Pipper,C. B.,Trolle,E.,Bro,R.,Larnkjaer,A.,Carlsen,E. M.,Molgaard,C.,Michaelsen,K. F. Maternal obesity and offspring dietary patterns at 9 months of age. Eur J Clin Nutr.2015;69:668-75. | DV
23 | Anderson, G. H.,Morson-Pasut, L. A.,Bryan, H.,Cleghorn, G.,Tanaka, P.,Yeung, D.,Zimmerman, B. Age of introduction of cow’s milk to infants. J Pediatr Gastroenterol Nutr.1985;4:692-8. | Design
24 | Anderson, V. P.,Cornwall, J.,Jack, S.,Gibson, R. S. Intakes from non-breastmilk foods for stunted toddlers living in poor urban villages of Phnom Penh, Cambodia, are inadequate. Matern Child Nutr.2008;4:146-59. | Design,Health status
25 | Andres, A.,Casey, P. H.,Cleves, M. A.,Badger, T. M. Body fat and bone mineral content of infants fed breast milk, cow’s milk formula, or soy formula during the first year of life. J Pediatr.2013;163:49-54. | IV
26 | Andres, A.,Cleves, M. A.,Bellando, J. B.,Pivik, R. T.,Casey, P. H.,Badger, T. M. Developmental status of 1-year-old infants fed breast milk, cow’s milk formula, or soy formula. Pediatrics.2012;129:1134-40. | IV
27 | Andrissi, L.,Mottini, G.,Sebastiani, V.,Boldrini, L.,Giuliani, A. Dietary habits and growth: an urban/rural comparison in the Andean region of Apurimac, Peru. Ann Ist Super Sanita.2013;49:340-6. | IV
28 | Anfield,L. Nutrition in the first year. Midwife Health Visit Community Nurse.1985;21:161-4. | Design
29 | Anzman-Frasca, S.,Liu, S.,Gates, K. M.,Paul, I. M.,Rovine, M. J.,Birch, L. L. Infants’ Transitions out of a Fussing/Crying State Are Modifiable and Are Related to Weight Status. Infancy.2013;18:662-686. | IV
30 | Armstrong, J.,Reilly, J. J. Breastfeeding and lowering the risk of childhood obesity. Lancet.2002;359:2003-4. | IV
31 | Arsenault,J. E.,Havel,P. J.,Lopez de Romana,D.,Penny,M. E.,Van Loan,M. D.,Brown,K. H. Longitudinal measures of circulating leptin and ghrelin concentrations are associated with the growth of young Peruvian children but are not affected by zinc supplementation. Am J Clin Nutr.2007;86:1111-9. | Health status
32 | Arvas, A.,Elgormus, Y.,Gur, E.,Alikasifoglu, M.,Celebi, A. Iron status in breast-fed full-term infants. Turk J Pediatr.2000;42:22-6. | IV
33 | Asha Bai, P. V.,Leela, M.,Subramaniam, V. R. Adequacy of breast milk for optimal growth of infants. Trop Geogr Med.1980;32:158-62. | IV
34 | Assuncao, M. L.,Ferreira, H. S.,Coutinho, S. B.,Santos, L. M.,Horta, B. L. Protective effect of breastfeeding against overweight can be detected as early as the second year of life: a study of children from one of the most socially-deprived areas of Brazil. J Health Popul Nutr.2015;33:85-91. | Design, Health status, IV
35 | Atladottir, H.,Thorsdottir, I. Energy intake and growth of infants in Iceland-a population with high frequency of breast-feeding and high birth weight. Eur J Clin Nutr.2000;54:695-701. | IV
36 | Auestad,N. Infant nutrition--brain development--disease in later life. An introduction. Dev Neurosci.2000;22:472-3. | Design
37 | Augusto,R. A.,Souza,J. M. Effectiveness of a supplementary feeding program in child weight gain. Rev Saude Publica.2010;44:793-801. | Design, IV
38 | Axelsson,I. E.,Jakobsson,I.,Raiha,N. C. Formula with reduced protein content: effects on growth and protein metabolism during weaning. Pediatr Res.1988;24:297-301. | IV
39 | Azad, M. B.,Konya, T.,Maughan, H.,Guttman, D. S.,Field, C. J.,Chari, R. S.,Sears, M. R.,Becker, A. B.,Scott, J. A.,Kozyrskyj, A. L. Gut microbiota of healthy Canadian infants: profiles by mode of delivery and infant diet at 4 months. Cmaj.2013;185:385-94. | DV
40 | Badger, T. Effects of soy infant formula on growth and development in the first year of life. Food Nutr Bull.2013;34:252-3. | Design, IV
41 | Bahamondes L,Bahamondes MV,Modesto W,Tilley IB,Magalhaes A,Pinto e Silva JL,Amaral E, Jr. Mishell DR. Effect of hormonal contraceptives during breastfeeding on infant’s milk ingestion and growth. Fertil Steril.2013;100:445-50. | IV
42 | Bai, K. I.,Sastry, V. N.,Reddy, C. C. A comparative study of feeding pattern of infants in rural and urban areas. Indian J Pediatr.1981;48:277-80. | Design, IV
43 | Balaban, G.,Motta, M. E.,Silva, G. A. Early weaning and other potential risk factors for overweight among preschool children. Clinics (Sao Paulo).2010;65:181-7. | IV, Age
44 | Balogun,T. A.,Lombard,M. J.,McLachlan,M. The nutrient intake of children aged 12-36 months living in two communities in the Breede Valley, Western Cape province, South Africa. South African Family Practice.2015;57:1-7 7p. | Design
45 | Baranowski, T.,Bryan, G. T.,Harrison, J. A.,Rassin, D. K.,Greaves, K. A.,Baranowski, J. H. Height, infant-feeding practices and cardiovascular functioning among 3 or 4 year old children in three ethnic groups. J Clin Epidemiol.1992;45:513-8. | DV
46 | Bartok, C. J.,Schaefer, E. W.,Beiler, J. S.,Paul, I. M. Role of body mass index and gestational weight gain in breastfeeding outcomes. Breastfeed Med.2012;7:448-56. | IV, DV
47 | Beal, V. A. Nutrition and growth-patterns of young children. ASDC J Dent Child.1983;50:139-41. | Design
48 | Begum, H. A.,Mascie-Taylor, C.,Nahar, S. The impact of food supplementation on infant weight gain in rural Bangladesh; an assessment of the Bangladesh Integrated Nutritional Program (BINP). Public Health Nutr.2007;10:49-54. | IV
49 | Beinner,M. A.,Velasquez-Melendez,G.,Pessoa,M. C.,Greiner,T. Iron-fortified rice is as efficacious as supplemental iron drops in infants and young children. J Nutr.2010;140:49-53. | IV, DV
50 | Ben,X. M.,Zhou,X. Y.,Zhao,W. H.,Yu,W. L.,Pan,W.,Zhang,W. L.,Wu,S. M.,Van Beusekom,C. M.,Schaafsma,A. Growth and development of term infants fed with milk with long-chain polyunsaturated fatty acid supplementation. Chin Med J (Engl).2004;117:1268-70. | IV
51 | Bennett,W. E.,Jr.,Hendrix,K. S.,Thompson-Fleming,R. T.,Downs,S. M.,Carroll,A. E. Early cow’s milk introduction is associated with failed personal-social milestones after 1 year of age. Eur J Pediatr.2014;173:887-92. | IV
52 | Bergmann, K. E.,Bergmann, R. L.,Von Kries, R.,Bohm, O.,Richter, R.,Dudenhausen, J. W.,Wahn, U. Early determinants of childhood overweight and adiposity in a birth cohort study: role of breast-feeding. Int J Obes Relat Metab Disord.2003;27:162-72. | IV
53 | Bernal, M. J.,Periago, M. J.,Martinez, R.,Ortuno, I.,Sanchez-Solis, M.,Ros, G.,Romero, F.,Abellan, P. Effects of infant cereals with different carbohydrate profiles on colonic function--randomised and double-blind clinical trial in infants aged between 6 and 12 months--pilot study. Eur J Pediatr.2013;172:1535-42. | IV
54 | Berni Canani R,Nocerino R,Terrin G,Frediani T,Lucarelli S,Cosenza L,Passariello A,Leone L,Granata V,Di Costanzo M,Pezzella V,Troncone R. Formula selection for management of children with cow’s milk allergy influences the rate of acquisition of tolerance: a prospective multicenter study. J Pediatr.2013;163:771-7.e1. | IV, DV
55 | Betoko, A.,Charles, M. A.,Hankard, R.,Forhan, A.,Bonet, M.,Regnault, N.,Botton, J.,Saurel-Cubizolles, M. J.,de Lauzon-Guillain, B. Determinants of infant formula use and relation with growth in the first 4 months. Matern Child Nutr.2014;10:267-79. | IV
56 | Betoko, A.,Charles, M. A.,Hankard, R.,Forhan, A.,Bonet, M.,Saurel-Cubizolles, M. J.,Heude, B.,de Lauzon-Guillain, B. Infant feeding patterns over the first year of life: influence of family characteristics. Eur J Clin Nutr.2013;67:631-7. | DV
57 | Bhandari, N.,Bahl, R.,Nayyar, B.,Khokhar, P.,Rohde, J. E.,Bhan, M. K. Food supplementation with encouragement to feed it to infants from 4 to 12 months of age has a small impact on weight gain. J Nutr.2001;131:1946-51. | Country
58 | Bhandari, N.,Mazumder, S.,Bahl, R.,Martines, J.,Black, R. E.,Bhan, M. K. An educational intervention to promote appropriate complementary feeding practices and physical growth in infants and young children in rural Haryana, India. J Nutr.2004;134:2342-8. | IV
59 | Bhatia, B. D.,Banerjee, D.,Agarwal, D. K.,Agarwal, K. N. Exterogestate growth: relationship with maternal body size and dietary intakes. Indian J Pediatr.1983;50:241-6. | Health status, IV
60 | Bindon, J. R.,Cabrera, C. Infant feeding patterns and growth of infants in American Samoa during the first year of life. Hum Biol.1988;60:81-92. | Design, IV, DV
61 | Bindon, J. R. The body build and composition of Samoan children: relationships to infant feeding patterns and infant weight-for-length status. Am J Phys Anthropol.1984;63:379-88. | IV
62 | Bindon, J. R. The influence of infant feeding patterns on growth of children in American Samoa. Med Anthropol.1985;9:183-95. | Country
63 | Birch,E. E.,Garfield,S.,Castaneda,Y.,Hughbanks-Wheaton,D.,Uauy,R.,Hoffman,D. Visual acuity and cognitive outcomes at 4 years of age in a double-blind, randomized trial of long-chain polyunsaturated fatty acid-supplemented infant formula. Early Hum Dev.2007;83:279-84. | IV
64 | Bisimwa, G.,Owino, V. O.,Bahwere, P.,Dramaix, M.,Donnen, P.,Dibari, F.,Collins, S. Randomized controlled trial of the effectiveness of a soybean-maize-sorghum-based ready-to-use complementary food paste on infant growth in South Kivu, Democratic Republic of Congo. Am J Clin Nutr.2012;95:1157-64. | IV
65 | Bjorke-Monsen, A. L. Is exclusive breastfeeding ensuring an optimal micronutrient status and psychomotor development in infants?. Clin Biochem.2014;47:714. | Design
66 | Block,S. L. Delayed introduction of solid foods to infants: not so fast!. Pediatr Ann.2013;42:143-7. | Design
67 | Bogen, D. L.,Hanusa, B. H.,Whitaker, R. C. The effect of breast-feeding with and without formula use on the risk of obesity at 4 years of age. Obes Res.2004;12:1527-35. | IV
68 | Bonuck, K.,Avraham, S. B.,Lo, Y.,Kahn, R.,Hyden, C. Bottle-weaning intervention and toddler overweight. J Pediatr.2014;164:306-12.e1-2. | IV
69 | Borschel, M. W.,Baggs, G. E.,Barrett-Reis, B. Growth of healthy term infants fed ready-to-feed and powdered forms of an extensively hydrolyzed casein-based infant formula: a randomized, blinded, controlled trial. Clin Pediatr (Phila).2014;53:585-92. | IV
70 | Boulton J. Nutrition in childhood and its relationships to early somatic growth, body fat, blood pressure, and physical fitness. Acta Paediatr Scand Suppl.1981;284:1-85. | Design,DV
71 | Brakohiapa, L. A.,Yartey, J.,Bille, A.,Harrison, E.,Quansah, E.,Armar, M. A.,Kishi, K.,Yamamoto, S. Does prolonged breastfeeding adversely affect a child’s nutritional status?. Lancet.1988;2:416-8. | IV, DV
72 | Brazionis, L.,Golley, R. K.,Mittinty, M. N.,Smithers, L. G.,Emmett, P.,Northstone, K.,Lynch, J. W. Diet spanning infancy and toddlerhood is associated with child blood pressure at age 7.5 y. Am J Clin Nutr.2013;97:1375-86. | DV
73 | Breij, L. M.,Mulder, M. T.,van Vark-van der Zee, L. C.,Hokken-Koelega, A. C. Appetite-regulating hormones in early life and relationships with type of feeding and body composition in healthy term infants. Eur J Nutr.2016. | IV
74 | Brekke, H. K.,van Odijk, J.,Ludvigsson, J. Predictors and dietary consequences of frequent intake of high-sugar, low-nutrient foods in 1-year-old children participating in the ABIS study. Br J Nutr.2007;97:176-81. | DV
75 | Brew,B. K.,Toelle,B. G.,Webb,K. L.,Almqvist,C.,Marks,G. B. Omega-3 supplementation during the first 5 years of life and later academic performance: a randomised controlled trial. Eur J Clin Nutr.2015;69:419-24. | IV
76 | Briend,A.,Bari,A. Breastfeeding improves survival, but not nutritional status, of 12-35 months old children in rural Bangladesh. Eur J Clin Nutr.1989;43:603-8. | Health status, IV
77 | Briend,A.,Darmon,N. Determining limiting nutrients by linear programming: A new approach to predict insufficient intakes from complementary foods. Pediatrics.2000;106:1288-9. | Design
78 | Brito,A.,Olivares,M.,Pizarro,T.,Rodriguez,L.,Hertrampf,E. Chilean complementary feeding program reduces anemia and improves iron status in children aged 11 to 18 months. Food Nutr Bull.2013;34:378-85. | Design
79 | Brown A,Lee MD. Early influences on child satiety-responsiveness: the role of weaning style. Pediatr Obes.2015;10:57-66. | IV
80 | Brown, A.,Lee, M. Breastfeeding during the first year promotes satiety responsiveness in children aged 18-24 months. Pediatr Obes.2012;7:382-90. | IV
81 | Brown,K. H.,Lopez de Romana,D.,Arsenault,J. E.,Peerson,J. M.,Penny,M. E. Comparison of the effects of zinc delivered in a fortified food or a liquid supplement on the growth, morbidity, and plasma zinc concentrations of young Peruvian children. Am J Clin Nutr.2007;85:538-47. | IV
82 | Brown,L. V.,Zeitlin,M. F.,Peterson,K. E.,Chowdhury,A. M.,Rogers,B. L.,Weld,L. H.,Gershoff,S. N. Evaluation of the impact of weaning food messages on infant feeding practices and child growth in rural Bangladesh. Am J Clin Nutr.1992;56:994-1003. | IV
83 | Brulotte, J.,Bukutu, C.,Vohra, S. Complementary, holistic, and integrative medicine: fish oils and neurodevelopmental disorders. Pediatr Rev.2009;30:e29-33. | Design
84 | Bulk-Bunschoten, A. M.,van Bodegom, S.,Reerink, J. D.,de Jong, P. C.,de Groot, C. J. Weight and weight gain at 4 months (The Netherlands 1998): influences of nutritional practices, socio-economic and ethnic factors. Paediatr Perinat Epidemiol.2002;16:361-9. | IV
85 | Burnham, L.,Matlak, S.,Makrigiorgos, G.,Braun, N.,Knapp, B. P.,Merewood, A. Breastfeeding and coffee consumption in children younger than 2 years in Boston, Massachusetts, USA. J Hum Lact.2015;31:267-72. | DV
86 | Caleyachetty A,Krishnaveni GV,Veena SR,Hill J,Karat SC,Fall CH,Wills AK. Breastfeeding duration, age of starting solids and high BMI risk and adiposity in Indian children. Matern Child Nutr.2013;9:199-216. | Design,Country
87 | Calvo,E. B.,Galindo,A. C.,Aspres,N. B. Iron status in exclusively breast-fed infants. Pediatrics.1992;90:375-9. | IV, DV
88 | Calvo,E.,Hertrampf,E.,Pablo,S.,Amar,M.,Stekel,A. Haemoglobin-fortified cereal: an alternative weaning food with high iron bioavailability. European journal of clinical nutrition.1989;43:237-43. | Design, DV
89 | Cameron, S. L.,Heath, A. L.,Gray, A. R.,Churcher, B.,Davies, R. S.,Newlands, A.,Galland, B. C.,Sayers, R. M.,Lawrence, J. A.,Taylor, B. J.,Taylor, R. W. Lactation Consultant Support from Late Pregnancy with an Educational Intervention at 4 Months of Age Delays the Introduction of Complementary Foods in a Randomized Controlled Trial. J Nutr.2015;145:1481-90. | DV
90 | Capozzi,L.,Russo,R.,Bertocco,F.,Ferrara,D.,Ferrara,M. Diet and iron deficiency in the first year of life: a retrospective study. Hematology.2010;15:410-3. | DV
91 | Capozzi,L.,Russo,R.,Bertocco,F.,Ferrara,D.,Ferrara,M. Effect on haematological and anthropometric parameters of iron supplementation in the first 2 years of life. Risks and benefits. Hematology.2011;16:261-4. | IV
92 | Carruth,B. R.,Nevling,W.,Skinner,J. D. Developmental and food profiles of infants born to adolescent and adult mothers. J Adolesc Health.1997;20:434-41. | IV, DV, Age
93 | Casiday, R. E.,Wright, C. M.,Panter-Brick, C.,Parkinson, K. N. Do early infant feeding patterns relate to breast-feeding continuation and weight gain? Data from a longitudinal cohort study. Eur J Clin Nutr.2004;58:1290-6. | IV
94 | Castillo-Duran,C.,Perales,C. G.,Hertrampf,E. D.,Marin,V. B.,Rivera,F. A.,Icaza,G. Effect of zinc supplementation on development and growth of Chilean infants. J Pediatr.2001;138:229-35. | IV
95 | Chaimay, B.,Ruagdaraganon, N.,Thinkhamrop, B.,Thinkhamrop, J. Association between infant feeding practices and first meaningful words at first year of life: a prospective cohort study of Thai children. Asia Pac J Public Health.2015;27:Np1071-84. | IV
96 | Chan,G. M.,Roberts,C. C.,Folland,D.,Jackson,R. Growth and bone mineralization of normal breast-fed infants and the effects of lactation on maternal bone mineral status. Am J Clin Nutr.1982;36:438-43. | IV
97 | Chang, S. Y.,He, W.,Chen, C. M. Complementary feeding and growth of infant and young child in China. Biomed Environ Sci.2008;21:264-8. | Design
98 | Chatterjee, M. K. Feeding pattern practised by the mothers attending an under five clinic. Indian J Public Health.1987;31:268-9. | Design
99 | Chavez A,Martinez C,Schlaepfer L. Health effects of supplementary feeding programs. Prog Clin Biol Res.1981;67:129-39. | Design
100 | Chawla, P.,Puri, R.,Pershad, D. Impact of pre-school supplementary feeding on mental abilities. Indian Pediatr.1983;20:513-6. | Age
101 | Chawla, P.,Puri, R. Impact of pre-school supplementary feeding programme on anthropometry. Indian Pediatr.1983;20:363-7. | Age
102 | Cheng, T. S.,Loy, S. L.,Cheung, Y. B.,Chan, J. K.,Pang, W. W.,Godfrey, K. M.,Gluckman, P. D.,Kwek, K.,Saw, S. M.,Chong, Y. S.,Lee, Y. S.,Lek, N.,Yap, F. Sexually dimorphic response to feeding mode in the growth of infants. Am J Clin Nutr.2016;103:398-405. | IV
103 | Chirmulay, D.,Nisal, R. Nutritional status of tribal underfive children in Ahmadnagar District, Maharashtra in relation to weaning/feeding practices. Indian Pediatr.1993;30:215-22. | Design
104 | Chitra, P. Development of banana-based weaning food mixes for infants and its nutritional quality evaluation. Rev Environ Health.2015;30:125-30. | IV
105 | Chivers, P.,Hands, B.,Parker, H.,Bulsara, M.,Beilin, L. J.,Kendall, G. E.,Oddy, W. H. Body mass index, adiposity rebound and early feeding in a longitudinal cohort (Raine Study). Int J Obes (Lond).2010;34:1169-76. | IV
106 | Cho, H. N.,Hong, S.,Lee, S. H.,Yum, H. Y. Nutritional status according to sensitized food allergens in children with atopic dermatitis. Allergy, Asthma and Immunology Research.2010;3:53-57. | Design, IV, DV
107 | Chorell,E.,Karlsson Videhult,F.,Hernell,O.,Antti,H.,West,C. E. Impact of probiotic feeding during weaning on the serum lipid profile and plasma metabolome in infants. Br J Nutr.2013;110:116-26. | IV
108 | Choudhury, N.,Bromage, S.,Alam, M. A.,Ahmed, A. M.,Islam, M. M.,Hossain, M. I.,Mahfuz, M.,Mondal, D.,Haque, M. R.,Ahmed, T. Intervention study shows suboptimal growth among children receiving a food supplement for five months in a slum in Bangladesh. Acta Paediatr.2016. | Health status, IV
109 | Christoffel, K. A pediatric perspective on vegetarian nutrition. Clin Pediatr (Phila).1981;20:632-43. | Design
110 | Christopher, G. C. First food: the essential role of breastfeeding. Breastfeed Med.2009;4 Suppl 1:S9-s10. | Design
111 | Chuang, C. H.,Yang, S. H.,Chang, P. J.,Chen, P. C.,Chen, Y. C. Dietary supplement intake by 6-month-old Taiwanese infants. J Pediatr Gastroenterol Nutr.2012;54:71-6. | DV
112 | Closa-Monasterolo, R.,Gispert-Llaurado, M.,Luque, V.,Ferre, N.,Rubio-Torrents, C.,Zaragoza-Jordana, M.,Escribano, J. Safety and efficacy of inulin and oligofructose supplementation in infant formula: results from a randomized clinical trial. Clin Nutr.2013;32:918-27. | IV
113 | Cloutier, M. M.,Wiley, J.,Wang, Z.,Grant, A.,Gorin, A. A. The Early Childhood Obesity Prevention Program (ECHO): an ecologically-based intervention delivered by home visitors for newborns and their mothers. BMC Public Health.2015;15:584. | Design
114 | Cockburn,F. Neonatal brain and dietary lipids. Arch Dis Child Fetal Neonatal Ed.1994;70:F1-2. | Design
115 | Cohen RJ,Brown KH,Canahuati J,Rivera LL,Dewey KG. Effects of age of introduction of complementary foods on infant breast milk intake, total energy intake, and growth: a randomised intervention study in Honduras. Lancet.1994;344:288-93. | Country
116 | Cohen, R. J.,Brown, K. H.,Canahuati, J.,Rivera, L. L.,Dewey, K. G. Determinants of growth from birth to 12 months among breast-fed Honduran infants in relation to age of introduction of complementary foods. Pediatrics.1995;96:504-10. | IV
117 | Coleman,B. L. Early introduction of non-formula cow’s milk to southern Ontario infants. Can J Public Health.2006;97:187-90. | IV, DV
118 | Colombo,J.,Carlson,S. E.,Cheatham,C. L.,Shaddy,D. J.,Kerling,E. H.,Thodosoff,J. M.,Gustafson,K. M.,Brez,C. Long-term effects of LCPUFA supplementation on childhood cognitive outcomes. Am J Clin Nutr.2013;98:403-12. | IV
119 | Coppi, S.,Iacoponi, F.,Fommei, C.,Strambi, M. Growth trend during the first six months of life in male infants with different type of feeding. Minerva Pediatr.2013;65:51-9. | IV
120 | Costom, B. H.,Shore, D. Effect of a comprehensive nutritional program on the growth and ponderosity of infants. Clin Pediatr (Phila).1983;22:105-11. | Design
121 | Courage, M. L.,McCloy, U. R.,Herzberg, G. R.,Andrews, W. L.,Simmons, B. S.,McDonald, A. C.,Mercer, C. N.,Friel, J. K. Visual acuity development and fatty acid composition of erythrocytes in full-term infants fed breast milk, commercial formula, or evaporated milk. J Dev Behav Pediatr.1998;19:9-17. | IV
122 | Cusack, R. Dietary management of obese children and adolescents. Pediatr Ann.1984;13:455, 458-9, 462-4. | Design
123 | Dagan, R.,Sofer, S.,Klish, W. J.,Hundt, G.,Saltz-Rennert, H.,Moses, S. W. Infant feeding practices among Bedouins in transition from seminomadic to settlement conditions in the Negev area of Israel. Isr J Med Sci.1984;20:1029-34. | Design, DV
124 | Dagnelie,P. C.,van Staveren,W. A.,Hautvast,J. G. Stunting and nutrient deficiencies in children on alternative diets. Acta Paediatr Scand Suppl.1991;374:111-8. | DV
125 | Dagnelie,P. C.,van Staveren,W. A.,Vergote,F. J.,Dingjan,P. G.,van den Berg,H.,Hautvast,J. G. Increased risk of vitamin B-12 and iron deficiency in infants on macrobiotic diets. Am J Clin Nutr.1989;50:818-24. | Design, DV
126 | Dagnelie,P. C.,van Staveren,W. A.,Verschuren,S. A.,Hautvast,J. G. Nutritional status of infants aged 4 to 18 months on macrobiotic diets and matched omnivorous control infants: a population-based mixed-longitudinal study. I. Weaning pattern, energy and nutrient intake. Eur J Clin Nutr.1989;43:311-23. | Design, DV
127 | Daniels, L. A.,Mallan, K. M.,Battistutta, D.,Nicholson, J. M.,Meedeniya, J. E.,Bayer, J. K.,Magarey, A. Child eating behavior outcomes of an early feeding intervention to reduce risk indicators for child obesity: the NOURISH RCT. Obesity (Silver Spring).2014;22:E104-11. | DV
128 | Daniels, L. A.,Mallan, K. M.,Battistutta, D.,Nicholson, J. M.,Perry, R.,Magarey, A. Evaluation of an intervention to promote protective infant feeding practices to prevent childhood obesity: outcomes of the NOURISH RCT at 14 months of age and 6 months post the first of two intervention modules. Int J Obes (Lond).2012;36:1292-8. | IV, DV
129 | Daniels, L. A.,Mallan, K. M.,Nicholson, J. M.,Battistutta, D.,Magarey, A. Outcomes of an early feeding practices intervention to prevent childhood obesity. Pediatrics.2013;132:e109-18. | IV
130 | Daniels, L. A.,Mallan, K. M.,Nicholson, J. M.,Thorpe, K.,Nambiar, S.,Mauch, C. E.,Magarey, A. An Early Feeding Practices Intervention for Obesity Prevention. Pediatrics.2015;136:e40-9. | IV
131 | Daniels, M. C.,Adair, L. S. Breast-feeding influences cognitive development in Filipino children. J Nutr.2005;135:2589-95. | IV
132 | Davidsson,L.,Sarker,S. A.,Jamil,K. A.,Sultana,S.,Hurrell,R. Regular consumption of a complementary food fortified with ascorbic acid and ferrous fumarate or ferric pyrophosphate is as useful as ferrous sulfate in maintaining hemoglobin concentrations >105 g/L in young Bangladeshi children. Am J Clin Nutr.2009;89:1815-20. | IV, DV
133 | de Hoog ML,van Eijsden M,Stronks K,Gemke RJ,Vrijkotte TG. The role of infant feeding practices in the explanation for ethnic differences in infant growth: the Amsterdam Born Children and their Development study. Br J Nutr.2011;106:1592-601. | Design
134 | de Kanashiro, H. C.,Brown, K. H.,Lopez de Romana, G.,Lopez, T.,Black, R. E. Consumption of food and nutrients by infants in Huascar (Lima), Peru. Am J Clin Nutr.1990;52:995-1004. | DV
135 | de Villiers, A.,Senekal, M. Determinants of growth failure in 12-24-month-old children in a high-density urban slum community in East London, South Africa. Eur J Clin Nutr.2002;56:1231-41. | Country
136 | de Zegher, F.,Sebastiani, G.,Diaz, M.,Sanchez-Infantes, D.,Lopez-Bermejo, A.,Ibanez, L. Body composition and circulating high-molecular-weight adiponectin and IGF-I in infants born small for gestational age: breast- versus formula-feeding. Diabetes.2012;61:1969-73. | Health status, IV
137 | Delport, S. D.,Becker, P. J.,Bergh, A. Growth, feeding practices and infections in black infants. S Afr Med J.1997;87:57-61. | IV, DV
138 | Dewey, K. G.,Cohen, R. J.,Rivera, L. L.,Canahuati, J.,Brown, K. H. Do exclusively breast-fed infants require extra protein?. Pediatr Res.1996;39:303-7. | IV
139 | Dewey, K. G.,Hawck, M. G.,Brown, K. H.,Lartey, A.,Cohen, R. J.,Peerson, J. M. Infant weight-for-length is positively associated with subsequent linear growth across four different populations. Matern Child Nutr.2005;1:11-20. | IV
140 | Dewey, K. G.,Heinig, M. J.,Nommsen, L. A.,Lonnerdal, B. Adequacy of energy intake among breast-fed infants in the DARLING study: relationships to growth velocity, morbidity, and activity levels. Davis Area Research on Lactation, Infant Nutrition and Growth. J Pediatr.1991;119:538-47. | IV
141 | Dewey, K. G.,Lonnerdal, B. Milk and nutrient intake of breast-fed infants from 1 to 6 months: relation to growth and fatness. J Pediatr Gastroenterol Nutr.1983;2:497-506. | IV
142 | Dewey, K. G.,Peerson, J. M.,Brown, K. H.,Krebs, N. F.,Michaelsen, K. F.,Persson, L. A.,Salmenpera, L.,Whitehead, R. G.,Yeung, D. L. Growth of breast-fed infants deviates from current reference data: a pooled analysis of US, Canadian, and European data sets. World Health Organization Working Group on Infant Growth. Pediatrics.1995;96:495-503. | Design
143 | Dewey, K. G.,Peerson, J. M.,Heinig, M. J.,Nommsen, L. A.,Lonnerdal, B.,Lopez de Romana, G.,de Kanashiro, H. C.,Black, R. E.,Brown, K. H. Growth patterns of breast-fed infants in affluent (United States) and poor (Peru) communities: implications for timing of complementary feeding. Am J Clin Nutr.1992;56:1012-8. | IV, DV
144 | Dewey, K. G. Complementary feeding and infant growth and body composition. Pediatrics.2000;106:1281. | Design
145 | Dewey,K. G.,Cohen,R. J.,Brown,K. H.,Rivera,L. L. Effects of exclusive breastfeeding for four versus six months on maternal nutritional status and infant motor development: results of two randomized trials in Honduras. J Nutr.2001;131:262-7. | Country
146 | Dewey,K. G.,Cohen,R. J.,Rivera,L. L.,Brown,K. H. Effects of age of introduction of complementary foods on iron status of breast-fed infants in Honduras. Am J Clin Nutr.1998;67:878-84. | DV
147 | Dewey,K. G.,Huffman,S. L. Maternal, infant, and young child nutrition: combining efforts to maximize impacts on child growth and micronutrient status. Food Nutr Bull.2009;30:S187-9. | Design
148 | Dewey,K. G.,Romero-Abal,M. E.,Quan de Serrano,J.,Bulux,J.,Peerson,J. M.,Eagle,P.,Solomons,N. W. Effects of discontinuing coffee intake on iron status of iron-deficient Guatemalan toddlers: a randomized intervention study. Am J Clin Nutr.1997;66:168-76. | DV
149 | Diaz, S.,Herreros, C.,Aravena, R.,Casado, M. E.,Reyes, M. V.,Schiappacasse, V. Breast-feeding duration and growth of fully breast-fed infants in a poor urban Chilean population. Am J Clin Nutr.1995;62:371-6. | IV, DV
150 | Doak, C. M.,van der Starre, R. E.,van Beusekom, I.,Campos Ponce, M.,Vossenaar, M.,Solomons, N. W. Earlier introduction of aguitas is associated with higher risk of stunting in infants and toddlers in the Western Highlands of Guatemala. Am J Clin Nutr.2013;97:631-6. | Design
151 | Domellof,M.,Cohen,R. J.,Dewey,K. G.,Hernell,O.,Rivera,L. L.,Lonnerdal,B. Iron supplementation of breast-fed Honduran and Swedish infants from 4 to 9 months of age. J Pediatr.2001;138:679-87. | IV, DV
152 | Dong,C.,Ge,P.,Ren,X.,Wang,J.,Fan,H.,Yan,X.,Yin,S. A. Prospective study on the effectiveness of complementary food supplements on improving status of elder infants and young children in the areas affected by Wenchuan earthquake. PLoS One.2013;8:e72711. | Design, Health status
153 | Donma, M. M.,Donma, O. Infant feeding and growth: a study on Turkish infants from birth to 6 months. Pediatr Int.1999;41:542-8. | IV
154 | Donma, M. M.,Donma, O. The influence of feeding patterns on head circumference among Turkish infants during the first 6 months of life. Brain Dev.1997;19:393-7. | IV
155 | Dubakiene, R.,Rudzeviciene, O.,Butiene, I.,Sezaite, I.,Petronyte, M.,Vaicekauskaite, D.,Zvirbliene, A. Studies on early allergic sensitization in the Lithuanian birth cohort. ScientificWorldJournal.2012;2012:909524. | IV, DV
156 | Dubois, L.,Girard, M. Breast-feeding, day-care attendance and the frequency of antibiotic treatments from 1.5 to 5 years: a population-based longitudinal study in Canada. Soc Sci Med.2005;60:2035-44. | IV, DV
157 | Dubois, L.,Girard, M. Social inequalities in infant feeding during the first year of life. The Longitudinal Study of Child Development in Quebec (LSCDQ 1998-2002). Public Health Nutr.2003;6:773-83. | IV, DV
158 | Dubowitz, T.,Levinson, D.,Peterman, J. N.,Verma, G.,Jacob, S.,Schultink, W. Intensifying efforts to reduce child malnutrition in India: an evaluation of the Dular program in Jharkhand, India. Food Nutr Bull.2007;28:266-73. | IV
159 | Duggan,C.,Penny,M. E.,Hibberd,P.,Gil,A.,Huapaya,A.,Cooper,A.,Coletta,F.,Emenhiser,C.,Kleinman,R. E. Oligofructose-supplemented infant cereal: 2 randomized, blinded, community-based trials in Peruvian infants. Am J Clin Nutr.2003;77:937-42. | IV
160 | Dunne,A. Nutrition in infancy: achieving nutrition needs for new mothers and children. Br J Community Nurs.2012;Suppl:S22. | Design
161 | Edmondson, L. What toddlers eat really matters. J Fam Health Care.2011;21:33-41. | Design
162 | El-Sayed H,Martines J,Rakha M,Zekry O,Abdel-Hak M,Abbas H. The effectiveness of the WHO training course on complementary feeding counseling in a primary care setting, Ismailia, Egypt. J Egypt Public Health Assoc.2014;89:1-8. | IV
163 | Elwood, P. C.,Haley, T. J.,Hughes, S. J.,Sweetnam, P. M.,Gray, O. P.,Davies, D. P. Child growth (0-5 years), and the effect of entitlement to a milk supplement. Arch Dis Child.1981;56:831-5. | IV
164 | Emmett,P. M.,Jones,L. R. Diet and growth in infancy: relationship to socioeconomic background and to health and development in the Avon Longitudinal Study of Parents and Children. Nutr Rev.2014;72:483-506. | Design
165 | Emond A,Drewett R,Blair P,Emmett P. Postnatal factors associated with failure to thrive in term infants in the Avon Longitudinal Study of Parents and Children. Arch Dis Child.2007;92:115-9. | IV
166 | Eneroth,H.,El Arifeen,S.,Persson,L. A.,Kabir,I.,Lonnerdal,B.,Hossain,M. B.,Ekstrom,E. C. Duration of exclusive breast-feeding and infant iron and zinc status in rural Bangladesh. J Nutr.2009;139:1562-7. | IV, DV
167 | Engelmann,M. D.,Davidsson,L.,Sandstrom,B.,Walczyk,T.,Hurrell,R. F.,Michaelsen,K. F. The influence of meat on nonheme iron absorption in infants. Pediatr Res.1998;43:768-73. | DV
168 | England, L.,Brenner, R.,Bhaskar, B.,Simons-Morton, B.,Das, A.,Revenis, M.,Mehta, N.,Clemens, J. Breastfeeding practices in a cohort of inner-city women: the role of contraindications. BMC Public Health.2003;3:28. | IV, DV
169 | Escribano, J.,Luque, V.,Ferre, N.,Mendez-Riera, G.,Koletzko, B.,Grote, V.,Demmelmair, H.,Bluck, L.,Wright, A.,Closa-Monasterolo, R. Effect of protein intake and weight gain velocity on body fat mass at 6 months of age: the EU Childhood Obesity Programme. Int J Obes (Lond).2012;36:548-53. | IV
170 | Esfarjani, F.,Azar, M. R.,Gafarpour, M. IDDM and early exposure of infant to cow’s milk and solid food. Indian J Pediatr.2001;68:107-10. | DV
171 | Evans, D.,Hansen, J. D.,Moodie, A. D.,van der Spuy, H. I. Intellectual development and nutrition. J Pediatr.1980;97:358-63. | Health status, IV
172 | Exl, B. M.,Deland, U.,Secretin, M. C.,Preysch, U.,Wall, M.,Shmerling, D. H. Improved general health status in an unselected infant population following an allergen reduced dietary intervention programme. The ZUFF-study-programme. Part I: Study design and 6-month nutritional behaviour. Eur J Nutr.2000;39:89-102. | DV
173 | Exl, B. M.,Deland, U.,Secretin, M. C.,Preysch, U.,Wall, M.,Shmerling, D. H. Improved general health status in an unselected infant population following an allergen-reduced dietary intervention programme: the ZUFF-STUDY-PROGRAMME. Part II: infant growth and health status to age 6 months. ZUg-FrauenFeld. Eur J Nutr.2000;39:145-56. | IV
174 | Faber,M.,Kvalsvig,J. D.,Lombard,C. J.,Benade,A. J. Effect of a fortified maize-meal porridge on anemia, micronutrient status, and motor development of infants. Am J Clin Nutr.2005;82:1032-9. | Country
175 | Faber,M. Dietary intake and anthropometric status differ for anaemic and non-anaemic rural South African infants aged 6-12 months. J Health Popul Nutr.2007;25:285-93. | Design
176 | Fabiansen, C.,Phelan, K. P.,Cichon, B.,Ritz, C.,Briend, A.,Michaelsen, K. F.,Friis, H.,Shepherd, S. Short children with a low midupper arm circumference respond to food supplementation: an observational study from Burkina Faso. Am J Clin Nutr.2016;103:415-21. | Health status
177 | Fabius, R. J.,Merritt, R. J.,Fleiss, P. M.,Ashley, J. M. Malnutrition associated with a formula of barley water, corn syrup, and whole milk. Am J Dis Child.1981;135:615-7. | Design
178 | Falkner, F. Introduction of food to infants. Genetic-environmental considerations. Am J Clin Nutr.1985;41:436-9. | Design
179 | Fall CH,Borja JB,Osmond C,Richter L,Bhargava SK,Martorell R,Stein AD,Barros FC,Victora CG. Infant-feeding patterns and cardiovascular risk factors in young adulthood: data from five cohorts in low- and middle-income countries. Int J Epidemiol.2011;40:47-62. | Design
180 | Farris, R. P.,Frank, G. C.,Webber, L. S.,Srinivasan, S. R.,Berenson, G. S. Influence of milk source on serum lipids and lipoproteins during the first year of life, Bogalusa heart study. Am J Clin Nutr.1982;35:42-9. | IV
181 | Farrow, C. V.,Blissett, J. Controlling feeding practices: cause or consequence of early child weight?. Pediatrics.2008;121:e164-9. | IV
182 | Farrow, C.,Blissett, J. Does maternal control during feeding moderate early infant weight gain?. Pediatrics.2006;118:e293-8. | IV
183 | Fawcett, J. N. Feeding from birth to 18 months. Nursing (Lond).1981:956-8. | Design
184 | Feldens CA,Vitolo MR,Rauber F,Cruz LN,Hilgert JB. Risk factors for discontinuing breastfeeding in southern Brazil: a survival analysis. Matern Child Health J.2012;16:1257-65. | IV, DV
185 | Feldens, C. A.,Ardenghi, T. M.,Cruz, L. N.,Scalco, G. P.,Vitolo, M. R. Advising mothers about breastfeeding and weaning reduced pacifier use in the first year of life: a randomized trial. Community Dent Oral Epidemiol.2013;41:317-26. | IV, DV
186 | Feldens, C. A.,Kramer, P. F.,Sequeira, M. C.,Rodrigues, P. H.,Vitolo, M. R. Maternal education is an independent determinant of cariogenic feeding practices in the first year of life. Eur Arch Paediatr Dent.2012;13:70-5. | DV
187 | Fergusson, D. M.,Woodward, L. J. Breast feeding and later psychosocial adjustment. Paediatr Perinat Epidemiol.1999;13:144-57. | IV
188 | Fernandes, T. A.,Werneck, G. L.,Hasselmann, M. H. Prepregnancy weight, weight gain during pregnancy, and exclusive breastfeeding in the first month of Life in Rio de Janeiro, Brazil. J Hum Lact.2012;28:55-61. | IV, DV
189 | Fernstrom, J. D.,Navia, J. L. Introduction to the workshop. Low-calorie sweeteners and weight control--what the science tells us. J Nutr.2012;142:1132s-3s. | Design
190 | Ferrara,M.,Bertocco,F.,Ricciardi,A.,Ferrara,D.,Incarnato,L.,Capozzi,L. Iron deficiency screening in the first three years of life: a three-decade-long retrospective case study. Hematology.2014;19:239-43. | DV
191 | Fildes, A.,van Jaarsveld, C. H.,Llewellyn, C.,Wardle, J.,Fisher, A. Parental control over feeding in infancy. Influence of infant weight, appetite and feeding method. Appetite.2015;91:101-6. | IV, DV
192 | Fisher, J. O.,Birch, L. L.,Smiciklas-Wright, H.,Picciano, M. F. Breast-feeding through the first year predicts maternal control in feeding and subsequent toddler energy intakes. J Am Diet Assoc.2000;100:641-6. | IV, DV
193 | Flax, V. L.,Bentley, M. E.,Chasela, C. S.,Kayira, D.,Hudgens, M. G.,Kacheche, K. Z.,Chavula, C.,Kourtis, A. P.,Jamieson, D. J.,van der Horst, C. M.,Adair, L. S. Lipid-based nutrient supplements are feasible as a breastmilk replacement for HIV-exposed infants from 24 to 48 weeks of age. J Nutr.2013;143:701-7. | Health status, IV
194 | Fomon SJ,Ziegler EE,Nelson SE,Edwards BB. Sweetness of diet and food consumption by infants. Proc Soc Exp Biol Med.1983;173:190-3. | IV, DV
195 | Fomon, S. J.,Rogers, R. R.,Ziegler, E. E.,Nelson, S. E.,Thomas, L. N. Indices of fatness and serum cholesterol at age eight years in relation to feeding and growth during early infancy. Pediatr Res.1984;18:1233-8. | IV, Date
196 | Forns,J.,Torrent,M.,Garcia-Esteban,R.,Caceres,A.,Pilar Gomila,M.,Martinez,D.,Morales,E.,Julvez,J.,Grimalt,J. O.,Sunyer,J. Longitudinal association between early life socio-environmental factors and attention function at the age 11 years. Environ Res.2012;117:54-9. | IV
197 | Foroushani, A. R.,Mohammad, K.,Mahmoodi, M.,Siassi, F. Effect of breastfeeding on cognitive performance in a British birth cohort. East Mediterr Health J.2010;16:202-8. | IV
198 | Franks, A. J.,Jurgensen, C. Nutrition and health in the first year of life on a Pacific atoll. Observations on Abemama Atoll, Central Pacific. Trans R Soc Trop Med Hyg.1985;79:681-4. | IV, DV
199 | Frederiksen,B. N.,Seifert,J.,Kroehl,M.,Lamb,M. M.,Milne,G. L.,Rewers,M.,Norris,J. M. Timing of solid food introduction is associated with urinary F2-isoprostane concentrations in childhood. Pediatric Research.2015;78:451-456. | DV
200 | Freeman, V.,van’t Hof, M.,Haschke, F. Patterns of milk and food intake in infants from birth to age 36 months: the Euro-growth study. J Pediatr Gastroenterol Nutr.2000;31 Suppl 1:S76-85. | DV
201 | Freeman,V. E.,Mulder,J.,van’t Hof,M. A.,Hoey,H. M.,Gibney,M. J. A longitudinal study of iron status in children at 12, 24 and 36 months. Public Health Nutr.1998;1:93-100. | DV
202 | Friel,J. K.,Andrews,W. L.,Simmons,B. S.,L’Abbe,M. R.,Mercer,C.,MacDonald,A.,McCloy,U. R. Evaluation of full-term infants fed an evaporated milk formula. Acta Paediatr.1997;86:448-53. | IV
203 | Froozani, M. D.,Malekafzali, H.,Bahrini, B. Growth of a group of low income infants in the first year of life. J Trop Pediatr.1980;26:96-8. | Design, IV
204 | Fuchs Iii, G. J.,Gastanaduy, A. S.,Suskind, R. M. Comparative metabolic study of older infants fed infant formula, transition formula, or whole cow’s milk. Nutrition Research.1992;12:1467-1478. | IV
205 | Fuchs, G. J.,Farris, R. P.,DeWier, M.,Hutchinson, S.,Strada, R.,Suskind, R. M. Effect of dietary fat on cardiovascular risk factors in infancy. Pediatrics.1994;93:756-63. | IV
206 | Gabriel, C. G.,Corso, A. C.,Caldeira, G. V.,Gimeno, S. G.,Schmitz Bde, A.,de Vasconcelos Fde, A. Overweight and obesity related factors in schoolchildren in Santa Catarina State, Brazil. Arch Latinoam Nutr.2010;60:332-9. | Design
207 | Gaffney, K. F.,Brito, A. V.,Kitsantas, P.,Kermer, D. A. Early Feeding Practices and Weight Status at One Year of Age: A Comparison of Hispanic Immigrant Mother-Infant Dyads with Participants of the Infant Feeding Practices Study II. Child Obes.2016. | IV, DV
208 | Gale, C.,Thomas, E. L.,Jeffries, S.,Durighel, G.,Logan, K. M.,Parkinson, J. R.,Uthaya, S.,Santhakumaran, S.,Bell, J. D.,Modi, N. Adiposity and hepatic lipid in healthy full-term, breastfed, and formula-fed human infants: a prospective short-term longitudinal cohort study. Am J Clin Nutr.2014;99:1034-40. | IV
209 | Galler, J. R.,Ramsey, F. C.,Harrison, R. H.,Brooks, R.,Weiskopf-Bock, S. Infant feeding practices in Barbados predict later growth. J Nutr.1998;128:1328-35. | IV
210 | Gallo PV. Physiological and behavioral consequences of maternal and post-weaning protein restriction. Physiol Behav.1981;26:77-84. | Design, Health status
211 | Galtry, J. Punching above its weight: does New Zealand’s responsibility for protecting, promoting, and supporting breastfeeding extend beyond its own borders?. J Hum Lact.2013;29:128-31. | Design
212 | Garza, C. The INTERGROWTH-21st project and the multicenter growth reference study: enhanced opportunities for monitoring growth from early pregnancy to 5 years of age. Breastfeed Med.2014;9:341-4. | Design
213 | Geuns, M.,Huisinga, C.,van Staveren, W. A.,Deurenberg, P.,Hautvast, J. G. Intakes of energy, protein and calcium and weaning pattern of a group of Dutch infants aged 6-12 months. Tijdschr Kindergeneeskd.1985;53:50-6. | Design, IV, DV
214 | Ghorashi,Z.,Nezami,N.,Ghalehgolab Behbahan,A.,Ghorashi,S. Supplemental food may not prevent iron-deficiency anemia in infants. Indian J Pediatr.2008;75:1121-4. | DV
215 | Ghosh,S.,Kilaru,A.,Ganapathy,S. Nutrition education and infant growth in rural Indian infants: narrowing the gender gap?. J Indian Med Assoc.2002;100:483-4, 486-8, 490. | IV
216 | Gianni, M. L.,Roggero, P.,Morlacchi, L.,Garavaglia, E.,Piemontese, P.,Mosca, F. Formula-fed infants have significantly higher fat-free mass content in their bodies than breastfed babies. Acta Paediatr.2014;103:e277-81. | IV
217 | Gibson,R. S.,Hotz,C. The adequacy of micronutrients in complementary foods. Pediatrics.2000;106:1298-9. | Design
218 | Gill, D. G.,Vincent, S.,Segal, D. S. Follow-on formula in the prevention of iron deficiency: a multicentre study. Acta Paediatr.1997;86:683-9. | IV
219 | Gillman, M. W.,Rifas-Shiman, S. L.,Camargo, C. A., Jr.,Berkey, C. S.,Frazier, A. L.,Rockett, H. R.,Field, A. E.,Colditz, G. A. Risk of overweight among adolescents who were breastfed as infants. Jama.2001;285:2461-7. | Design
220 | Gokcay, G.,Turan, J. M.,Partalci, A.,Neyzi, O. Growth of infants during the first year of life according to feeding regimen in the first 4 months. J Trop Pediatr.2003;49:6-12. | IV
221 | Golley,R. K.,Smithers,L. G.,Mittinty,M. N.,Brazionis,L.,Emmett,P.,Northstone,K.,Campbell,K.,McNaughton,S. A.,Lynch,J. W. An index measuring adherence to complementary feeding guidelines has convergent validity as a measure of infant diet quality. J Nutr.2012;142:901-8. | IV, DV
222 | Gomez Santos, S. F.,Estevez Santiago, R.,Palacios Gil-Antunano, N.,Leis Trabazo, M. R.,Tojo Sierra, R.,Cuadrado Vives, C.,Beltran de Miguel, B.,Avila Torres, J. M.,Varela Moreiras, G.,Casas Esteve, R. THAO-CHILD HEALTH PROGRAMME: COMMUNITY BASED INTERVENTION FOR HEALTHY LIFESTYLES PROMOTION TO CHILDREN AND FAMILIES: RESULTS OF A COHORT STUDY. Nutr Hosp.2015;32:2584-7. | Age
223 | Gomez-Sanchiz, M.,Canete, R.,Rodero, I.,Baeza, J. E.,Avila, O. Influence of breast-feeding on mental and psychomotor development. Clin Pediatr (Phila).2003;42:35-42. | IV
224 | Gomez-Sanchiz, M.,Canete, R.,Rodero, I.,Baeza, J. E.,Gonzalez, J. A. Influence of breast-feeding and parental intelligence on cognitive development in the 24-month-old child. Clin Pediatr (Phila).2004;43:753-61. | IV
225 | Gong, Y. H.,Ji, C. Y.,Zheng, X. X.,Shan, J. P.,Hou, R. Correlation of 4-month infant feeding modes with their growth and iron status in Beijing. Chin Med J (Engl).2008;121:392-8. | IV
226 | Gooze, R. A.,Anderson, S. E.,Whitaker, R. C. Prolonged bottle use and obesity at 5.5 years of age in US children. J Pediatr.2011;159:431-6. | IV
227 | Greene, L. C.,Lucas, A.,Livingstone, M. B.,Harland, P. S.,Baker, B. A. Relationship between early diet and subsequent cognitive performance during adolescence. Biochem Soc Trans.1995;23:376s. | Design, IV
228 | Greer,F. R.,Searcy,J. E.,Levin,R. S.,Steichen,J. J.,Steichen-Asche,P. S.,Tsang,R. C. Bone mineral content and serum 25-hydroxyvitamin D concentrations in breast-fed infants with and without supplemental vitamin D: one-year follow-up. J Pediatr.1982;100:919-22. | IV
229 | Grote, V.,von Kries, R.,Closa-Monasterolo, R.,Scaglioni, S.,Gruszfeld, D.,Sengier, A.,Langhendries, J. P.,Koletzko, B. Protein intake and growth in the first 24 months of life. J Pediatr Gastroenterol Nutr.2010;51 Suppl 3:S117-8. | Design, IV
230 | Gruszfeld, D.,Weber, M.,Nowakowska-Rysz, M.,Janas, R.,Kozlik-Feldmann, R.,Xhonneux, A.,Carlier, C.,Riva, E.,Verduci, E.,Closa-Monasterolo, R.,Escribano, J.,Dobrzanska, A.,Koletzko, B. Protein intake in infancy and carotid intima media thickness at 5 years--a secondary analysis from a randomized trial. Ann Nutr Metab.2015;66:51-9. | IV
231 | Gubbels, J. S.,Thijs, C.,Stafleu, A.,van Buuren, S.,Kremers, S. P. Association of breast-feeding and feeding on demand with child weight status up to 4 years. Int J Pediatr Obes.2011;6:e515-22. | IV, DV
232 | Gunderson, E. P.,Hurston, S. R.,Dewey, K. G.,Faith, M. S.,Charvat-Aguilar, N.,Khoury, V. C.,Nguyen, V. T.,Quesenberry, C. P., Jr. The study of women, infant feeding and type 2 diabetes after GDM pregnancy and growth of their offspring (SWIFT Offspring study): prospective design, methodology and baseline characteristics. BMC Pregnancy Childbirth.2015;15:150. | Design
233 | Gunnarsdottir I,Schack-Nielsen L,Michaelsen KF,Sorensen TI,Thorsdottir I. Infant weight gain, duration of exclusive breast-feeding and childhood BMI - two similar follow-up cohorts. Public Health Nutr.2010;13:201-7. | IV
234 | Gunnarsdottir, I.,Thorsdottir, I. Relationship between growth and feeding in infancy and body mass index at the age of 6 years. Int J Obes Relat Metab Disord.2003;27:1523-7. | IV
235 | Gunther, A. L.,Buyken, A. E.,Kroke, A. Protein intake during the period of complementary feeding and early childhood and the association with body mass index and percentage body fat at 7 y of age. Am J Clin Nutr.2007;85:1626-33. | IV
236 | Gunther, A. L.,Buyken, A. E.,Kroke, A. The influence of habitual protein intake in early childhood on BMI and age at adiposity rebound: results from the DONALD Study. Int J Obes (Lond).2006;30:1072-9. | IV
237 | Gurnida, D. A.,Rowan, A. M.,Idjradinata, P.,Muchtadi, D.,Sekarwana, N. Association of complex lipids containing gangliosides with cognitive development of 6-month-old infants. Early Hum Dev.2012;88:595-601. | IV
238 | Hamilton, K.,Daniels, L.,White, K. M.,Murray, N.,Walsh, A. Predicting mothers’ decisions to introduce complementary feeding at 6 months. An investigation using an extended theory of planned behaviour. Appetite.2011;56:674-81. | IV, DV
239 | Hammer, L. D.,Bryson, S.,Agras, W. S. Development of feeding practices during the first 5 years of life. Arch Pediatr Adolesc Med.1999;153:189-94. | DV
240 | Han,Y. H.,Yon,M.,Han,H. S.,Johnston,K. E.,Tamura,T.,Hyun,T. Zinc status and growth of Korean infants fed human milk, casein-based, or soy-based formula: three-year longitudinal study. Nutr Res Pract.2011;5:46-51. | IV
241 | Harbild, H. L.,Harslof, L. B.,Christensen, J. H.,Kannass, K. N.,Lauritzen, L. Fish oil-supplementation from 9 to 12 months of age affects infant attention in a free-play test and is related to change in blood pressure. Prostaglandins Leukot Essent Fatty Acids.2013;89:327-33. | IV
242 | Harit D,Faridi MM,Aggarwal A,Sharma SB. Lipid profile of term infants on exclusive breastfeeding and mixed feeding: a comparative study. Eur J Clin Nutr.2008;62:203-9. | IV
243 | Harrington,M.,Hotz,C.,Zeder,C.,Polvo,G. O.,Villalpando,S.,Zimmermann,M. B.,Walczyk,T.,Rivera,J. A.,Hurrell,R. F. A comparison of the bioavailability of ferrous fumarate and ferrous sulfate in non-anemic Mexican women and children consuming a sweetened maize and milk drink. Eur J Clin Nutr.2011;65:20-5. | IV, DV
244 | Harris,R. Inadequate diets: short- and long-term problems. J Fam Health Care.2002;12:6. | Design
245 | Hasan,J.,Ray,J.,Khan,Z. Role of weaning in the nutritional status of infant--a longitudinal study in the rural area of Aligarh. J Indian Med Assoc.1996;94:169, 215. | Design, IV, DV
246 | Haschke, F.,Pietschnig, B.,Vanura, H.,Heil, M.,Steffan, I.,Hobiger, G.,Schuster, E.,Camaya, Z. Iron intake and iron nutritional status of infants fed iron-fortified beikost with meat. Am J Clin Nutr.1988;47:108-12. | IV
247 | Hawley, N. L.,Johnson, W.,Nu’usolia, O.,McGarvey, S. T. The contribution of feeding mode to obesogenic growth trajectories in American Samoan infants. Pediatr Obes.2014;9:e1-e13. | IV
248 | Hay,G.,Johnston,C.,Whitelaw,A.,Trygg,K.,Refsum,H. Folate and cobalamin status in relation to breastfeeding and weaning in healthy infants. Am J Clin Nutr.2008;88:105-14. | DV
249 | Hediger, M. L.,Overpeck, M. D.,Ruan, W. J.,Troendle, J. F. Early infant feeding and growth status of US-born infants and children aged 4-71 mo: analyses from the third National Health and Nutrition Examination Survey, 1988-1994. Am J Clin Nutr.2000;72:159-67. | Design, IV
250 | Hegar, B.,Dewanti, N. R.,Kadim, M.,Alatas, S.,Firmansyah, A.,Vandenplas, Y. Natural evolution of regurgitation in healthy infants. Acta Paediatr.2009;98:1189-93. | IV, DV
251 | Heine, W.,Lapsien, C. Influence of early breast milk and formula feeding on body weight in children born in Rostock since 1945. Bibl Nutr Dieta.1982:17-8. | Design
252 | Herbst, A.,Diethelm, K.,Cheng, G.,Alexy, U.,Icks, A.,Buyken, A. E. Direction of associations between added sugar intake in early childhood and body mass index at age 7 years may depend on intake levels. J Nutr.2011;141:1348-54. | IV
253 | Hess,S. Y.,Abbeddou,S.,Jimenez,E. Y.,Somé,J. W.,Vosti,S. A.,Ouédraogo,Z. P.,Guissou,R. M.,Ouédraogo,J. B.,Brown,K. H. Small-quantity lipid-based nutrient supplements, regardless of their zinc content, increase growth and reduce the prevalence of stunting and Wasting in young burkinabe children: A cluster-randomized trial. PLoS ONE.2015;10. | IV, Country
254 | Hettiarachchi,M.,Lekamwasam,S.,Liyanage,C. Long-term cereal-based nutritional supplementation improved the total spine bone mineral density amongst Sri Lankan preschool children: a randomized controlled study. J Pediatr Endocrinol Metab.2010;23:555-63. | IV, Age
255 | Hijazi, S. S.,Abulaban, A.,Waterlow, J. C. The duration for which exclusive breast-feeding is adequate. A study in Jordan. Acta Paediatr Scand.1989;78:23-8. | IV
256 | Hillis, S. D.,Weigle, K.,Miranda, C. M.,McCann, M.,Bender, D.,Stewart, P. Supplementary feeding in Colombian child-care centers and growth velocity. Pediatrics.1994;94:1066-9. | IV
257 | Hitchcock, N. E.,Gracey, M.,Gilmour, A. I. The growth of breast fed and artificially fed infants from birth to twelve months. Acta Paediatr Scand.1985;74:240-5. | IV
258 | Hitchcock, N. E.,McGuiness, D.,Gracey, M. Growth and feeding practices of Western Australian infants. Med J Aust.1982;1:372-6. | Design, IV, DV, Date
259 | Hitchcock, N. E.,Owles, E. N.,Gracey, M. Breast feeding and growth of healthy infants. Med J Aust.1981;2:536-7. | IV, DV, Date
260 | Hoffman, D. R.,Garfield, S.,Morale, S. E.,Bosworth, R. G.,Castaneda, Y. S.,Wheaton, D. K. H.,Theuer, R. C.,Birch, E. E. Visual and neural development of breast-fed infants receiving docosahexaenoic acid (dha)-enriched baby food: a randomized clinical trial. Iovs.2004;45:ARVO E-abstract 3510. | Design
261 | Hokama,T. Levels of serum ferritin and total body iron among infants with different feeding regimens. Acta Paediatr Jpn.1993;35:298-301. | IV, DV
262 | Holgerson PL,Vestman NR,Claesson R,Ohman C,Domellof M,Tanner AC,Hernell O,Johansson I. Oral microbial profile discriminates breast-fed from formula-fed infants. J Pediatr Gastroenterol Nutr.2013;56:127-36. | Design, IV, DV
263 | Hop le, T.,Berger, J. Multiple micronutrient supplementation improves anemia, micronutrient nutrient status, and growth of Vietnamese infants: double-blind, randomized, placebo-controlled trial. J Nutr.2005;135:660s-665s. | IV
264 | Hop, L. T.,Gross, R.,Giay, T.,Sastroamidjojo, S.,Schultink, W.,Lang, N. T. Premature complementary feeding is associated with poorer growth of vietnamese children. J Nutr.2000;130:2683-90. | Country
265 | Hop, L. T.,Gross, R.,Giay, T.,Schultink, W.,Thuan, B. T.,Sastroamidjojo, S. Longitudinal observation of growth of Vietnamese children in Hanoi, Vietnam from birth to 10 years of age. Eur J Clin Nutr.1997;51:164-71. | IV, DV
266 | Hopkins, D.,Steer, C. D.,Northstone, K.,Emmett, P. M. Effects on childhood body habitus of feeding large volumes of cow or formula milk compared with breastfeeding in the latter part of infancy. Am J Clin Nutr.2015;102:1096-103. | IV
267 | Hopkins,D.,Emmett,P.,Steer,C.,Rogers,I.,Noble,S.,Emond,A. Infant feeding in the second 6 months of life related to iron status: an observational study. Arch Dis Child.2007;92:850-4. | DV
268 | Hoppe, C.,Molgaard, C.,Thomsen, B. L.,Juul, A.,Michaelsen, K. F. Protein intake at 9 mo of age is associated with body size but not with body fat in 10-y-old Danish children. Am J Clin Nutr.2004;79:494-501. | IV
269 | Horodynski, M. A.,Baker, S.,Van Egeren, L.,Olson, B.,Brophy-Herb, H.,Auld, G. The healthy babies curriculum. J Nutr Educ Behav.2014;46:151-2. | Design, IV
270 | Horta, B. L.,Bas, A.,Bhargava, S. K.,Fall, C. H.,Feranil, A.,de Kadt, J.,Martorell, R.,Richter, L. M.,Stein, A. D.,Victora, C. G. Infant feeding and school attainment in five cohorts from low- and middle-income countries. PLoS One.2013;8:e71548. | Design
271 | Horwood, L. J.,Fergusson, D. M. Breastfeeding and later cognitive and academic outcomes. Pediatrics.1998;101:E9. | IV
272 | Hosaka, M.,Asayama, K.,Staessen, J. A.,Ohkubo, T.,Hayashi, K.,Tatsuta, N.,Kurokawa, N.,Satoh, M.,Hashimoto, T.,Hirose, T.,Obara, T.,Metoki, H.,Inoue, R.,Kikuya, M.,Nakai, K.,Imai, Y.,Satoh, H. Breastfeeding leads to lower blood pressure in 7-year-old Japanese children: Tohoku Study of Child Development. Hypertens Res.2013;36:117-22. | IV, DV
273 | Hudara S,Mimouni F,Rachman Y,Dayan B,Silbermintz A,Turner D. Retrospective cohort study of a new infant formula during the first 6 months of life: reflections on growth curves, human milk and formula feeding. Isr Med Assoc J.2010;12:676-80. | IV
274 | Hurley, K. M.,Black, M. M. Introduction to a supplement on responsive feeding: promoting healthy growth and development for infants and toddlers. J Nutr.2011;141:489. | Design
275 | Husaini, M. A.,Karyadi, L.,Husaini, Y. K.,Sandjaja,,Karyadi, D.,Pollitt, E. Developmental effects of short-term supplementary feeding in nutritionally-at-risk Indonesian infants. Am J Clin Nutr.1991;54:799-804. | Country
276 | Inostroza, J.,Haschke, F.,Steenhout, P.,Grathwohl, D.,Nelson, S. E.,Ziegler, E. E. Low-protein formula slows weight gain in infants of overweight mothers. J Pediatr Gastroenterol Nutr.2014;59:70-7. | IV
277 | Isherwood,R. J.,Dimond,C.,Longhurst,S. Breast feeding and weaning practices in relation to nutritional status of under-5 children in north Bangladesh. J Trop Pediatr.1988;34:28-31. | Design
278 | Islam, M. M.,Peerson, J. M.,Ahmed, T.,Dewey, K. G.,Brown, K. H. Effects of varied energy density of complementary foods on breast-milk intakes and total energy consumption by healthy, breastfed Bangladeshi children. Am J Clin Nutr.2006;83:851-8. | IV, DV
279 | Jackson, D. A.,Imong, S. M.,Wongsawasdii, L.,Silprasert, A.,Preunglampoo, S.,Leelapat, P.,Drewett, R. F.,Amatayakul, K.,Baum, J. D. Weaning practices and breast-feeding duration in Northern Thailand. Br J Nutr.1992;67:149-64. | IV, DV
280 | Jackson,M. I. Early childhood WIC participation, cognitive development and academic achievement. Soc Sci Med.2015;126:145-53. | IV
281 | Jacobson, S. W.,Chiodo, L. M.,Jacobson, J. L. Breastfeeding effects on intelligence quotient in 4- and 11-year-old children. Pediatrics.1999;103:e71. | IV
282 | Jain,V.,Klein,B. P.,Nash,M.,Chapman-Novakofski,K. Two feasibility studies for introduction of multimicronutrient soy/whey-based supplements in rural homes in Honduras. Journal of Hunger and Environmental Nutrition.2011;6:247-263. | IV
283 | Jansen,G.R.,O’B Hourihane. The nutritional status of preschool children in Egypt. World Rev Nutr Diet.1985;45:42-67. | Design
284 | Jatanasen,A.,Sacholvicharn,V.,Ongkulna,P. An evaluation of supplementary feedings of Thai infants in urban slum communities: effect on growth, health and nutritional status. J Med Assoc Thai.1983;66 Suppl 1:20-9. | Design, Health status
285 | Jensen, B. W.,Nichols, M.,Allender, S.,de Silva-Sanigorski, A.,Millar, L.,Kremer, P.,Lacy, K.,Swinburn, B. Inconsistent associations between sweet drink intake and 2-year change in BMI among Victorian children and adolescents. Pediatr Obes.2013;8:271-83. | Age
286 | Jensen, S. M.,Ritz, C.,Ejlerskov, K. T.,Molgaard, C.,Michaelsen, K. F. Infant BMI peak, breastfeeding, and body composition at age 3 y. Am J Clin Nutr.2015;101:319-25. | IV
287 | Jensen,C. L.,Prager,T. C.,Zou,Y.,Fraley,J. K.,Maude,M.,Anderson,R. E.,Heird,W. C. Effects of maternal docosahexaenoic acid supplementation on visual function and growth of breast-fed term infants. Lipids.1999;34 Suppl:S225. | Design, IV
288 | Jones, G.,Hynes, K. L.,Dwyer, T. The association between breastfeeding, maternal smoking in utero, and birth weight with bone mass and fractures in adolescents: a 16-year longitudinal study. Osteoporos Int.2013;24:1605-11. | IV
289 | Jones, G.,Riley, M.,Dwyer, T. Breastfeeding in early life and bone mass in prepubertal children: a longitudinal study. Osteoporos Int.2000;11:146-52. | IV
290 | Jooste, P. L.,Rossouw, L. J.,Steenkamp, H. J.,Rossouw, J. E.,Swanepoel, A. S.,Charlton, D. O. Effect of breast feeding on the plasma cholesterol and growth of infants. J Pediatr Gastroenterol Nutr.1991;13:139-42. | IV
291 | Joseph, N.,Unnikrishnan, B.,Naik, V. A.,Mahantshetti, N. S.,Mallapur, M. D.,Kotian, S. M.,Nelliyanil, M. Infant rearing practices in South India: a longitudinal study. J Family Med Prim Care.2013;2:37-43. | Country
292 | Joshi N,Agho KE,Dibley MJ,Senarath U,Tiwari K. Determinants of inappropriate complementary feeding practices in young children in Nepal: secondary data analysis of Demographic and Health Survey 2006. Matern Child Nutr.2012;8 Suppl 1:45-59. | Design, Country
293 | Juez, G.,Diaz, S.,Casado, M. E.,Duran, E.,Salvatierra, A. M.,Peralta, O.,Croxatto, H. B. Growth pattern of selected urban Chilean infants during exclusive breast-feeding. Am J Clin Nutr.1983;38:462-8. | IV
294 | Jung, E.,Czajka-Narins, D. M. Birth weight doubling and tripling times: an updated look at the effects of birth weight, sex, race and type of feeding. Am J Clin Nutr.1985;42:182-9. | IV
295 | Kagura, J.,Feeley, A. B.,Micklesfield, L. K.,Pettifor, J. M.,Norris, S. A. Association between infant nutrition and anthropometry, and pre-pubertal body composition in urban South African children. J Dev Orig Health Dis.2012;3:415-23. | Country
296 | Kainonen E,Rautava S,Isolauri E. Immunological programming by breast milk creates an anti-inflammatory cytokine milieu in breast-fed infants compared to formula-fed infants. Br J Nutr.2013;109:1962-70. | IV, DV
297 | Kajantie, E.,Barker, D. J.,Osmond, C.,Forsen, T.,Eriksson, J. G. Growth before 2 years of age and serum lipids 60 years later: the Helsinki Birth Cohort study. Int J Epidemiol.2008;37:280-9. | DV
298 | Kallio, M. J.,Salmenpera, L.,Siimes, M. A.,Perheentupa, J.,Miettinen, T. A. Tracking of serum cholesterol and lipoprotein levels from the first year of life. Pediatrics.1993;91:949-54. | IV, DV
299 | Kallio,M. J.,Salmenpera,L.,Siimes,M. A.,Perheentupa,J.,Miettinen,T. A. Exclusive breast-feeding and weaning: effect on serum cholesterol and lipoprotein concentrations in infants during the first year of life. Pediatrics.1992;89:663-6. | IV, DV
300 | Karaolis-Danckert, N.,Buyken, A. E.,Kulig, M.,Kroke, A.,Forster, J.,Kamin, W.,Schuster, A.,Hornberg, C.,Keil, T.,Bergmann, R. L.,Wahn, U.,Lau, S. How pre- and postnatal risk factors modify the effect of rapid weight gain in infancy and early childhood on subsequent fat mass development: results from the Multicenter Allergy Study 90. Am J Clin Nutr.2008;87:1356-64. | IV
301 | Karlsland Akeson, P. K.,Axelsson, I. E.,Raiha, N. C.,Warm, A.,Minoli, I.,Moro, G. Protein intake and metabolism in formula-fed infants given Swedish or Italian weaning foods. Acta Paediatr.2000;89:158-64. | IV
302 | Karlsson Videhult, F.,Ohlund, I.,Stenlund, H.,Hernell, O.,West, C. E. Probiotics during weaning: a follow-up study on effects on body composition and metabolic markers at school age. Eur J Nutr.2015;54:355-63. | IV
303 | Kattelmann,K. K.,Ho,M.,Specker,B. L. Effect of timing of introduction of complementary foods on iron and zinc status of formula fed infants at 12, 24, and 36 months of age. J Am Diet Assoc.2001;101:443-7. | DV
304 | Kavanagh, K. F.,Cohen, R. J.,Heinig, M. J.,Dewey, K. G. Educational intervention to modify bottle-feeding behaviors among formula-feeding mothers in the WIC program: impact on infant formula intake and weight gain. J Nutr Educ Behav.2008;40:244-50. | IV
305 | Kavle, J. A.,Flax, V. L.,Abdelmegeid, A.,Salah, F.,Hafez, S.,Ramzy, M.,Hamed, D.,Saleh, G.,Galloway, R. Factors associated with early growth in Egyptian infants: implications for addressing the dual burden of malnutrition. Matern Child Nutr.2016;12:139-51. | Country
306 | Kersting, M.,Alexy, U.,Sichert-Hellert, W.,Manz, F.,Schoch, G. Measured consumption of commercial infant food products in German infants: results from the DONALD study. Dortmund Nutritional and Anthropometrical Longitudinally Designed. J Pediatr Gastroenterol Nutr.1998;27:547-52. | DV
307 | Kesaree, N.,Shivamurty, K. S.,Prakash, B. S.,Ramachandra,,Haridas, C. K. Feeding pattern of infants in Devangere. Indian J Pediatr.1981;48:281-4. | Design, IV
308 | Khaldi, F.,Bouguerra, F. Feeding practices, growth, and morbidity in Tunisia. Pediatrics.2000;106:1275-6. | Design, Date
309 | Khan, A. I.,Kabir, I.,Hawkesworth, S.,Ekström, E. C.,Arifeen, S.,Frongillo, E. A.,Persson, L. A. Early invitation to food and/or multiple micronutrient supplementation in pregnancy does not affect body composition in offspring at 54 months: Follow-up of the MINIMat randomised trial, Bangladesh. Maternal and Child Nutrition.2015;11:385-397. | IV, Age
310 | Khan, M. U. Breastfeeding, growth and diarrhoea in rural Bangladesh children. Hum Nutr Clin Nutr.1984;38:113-9. | IV
311 | Khan, M. Infant feeding practices in rural Meheran, Comilla, Bangladesh. Am J Clin Nutr.1980;33:2356-64. | IV, DV
312 | Kholdi N,Zayeri F,Bagheban AA,Khodakarim S,Ramezankhani A. A study of growth failure and its related factors in children from 0 to 2 years in Tehran, Iran. Turk J Pediatr.2012;54:38-44. | Design
313 | Kiefte-de Jong, J. C.,de Vries, J. H.,Escher, J. C.,Jaddoe, V. W.,Hofman, A.,Raat, H.,Moll, H. A. Role of dietary patterns, sedentary behaviour and overweight on the longitudinal development of childhood constipation: the Generation R study. Matern Child Nutr.2013;9:511-23. | DV
314 | Kilaru, A.,Griffiths, P. L.,Ganapathy, S.,Ghosh, S. Community-based nutrition education for improving infant growth in rural Karnataka. Indian Pediatr.2005;42:425-32. | IV
315 | King,S.,Prawitz,A. D.,Umoren,J.,O’Gorman,T. The impact of high diastase malted barley flour on weight and height of malnourished children in Panama. Journal of Hunger and Environmental Nutrition.2007;1:23-35. | Health status, Age
316 | Klag, E. A.,McNamara, K.,Geraghty, S. R.,Keim, S. A. Associations Between Breast Milk Feeding, Introduction of Solid Foods, and Weight Gain in the First 12 Months of Life. Clin Pediatr (Phila).2015;54:1059-67. | Design
317 | Kleinman, R. E. Complementary feeding and neuromuscular development. Pediatrics.2000;106:1279. | Design
318 | Kolacek, S.,Kapetanovic, T.,Zimolo, A.,Luzar, V. Early determinants of cardiovascular risk factors in adults. A. Plasma lipids. Acta Paediatr.1993;82:699-704. | DV
319 | Koletzko, B.,Dokoupil, K.,Reitmayr, S.,Weimert-Harendza, B.,Keller, E. Dietary fat intakes in infants and primary school children in Germany. Am J Clin Nutr.2000;72:1392s-1398s. | IV, DV
320 | Koletzko, B.,von Kries, R.,Closa, R.,Escribano, J.,Scaglioni, S.,Giovannini, M.,Beyer, J.,Demmelmair, H.,Anton, B.,Gruszfeld, D.,Dobrzanska, A.,Sengier, A.,Langhendries, J. P.,Rolland Cachera, M. F.,Grote, V. Can infant feeding choices modulate later obesity risk?. Am J Clin Nutr.2009;89:1502s-1508s. | Design, IV
321 | Koletzko, B.,von Kries, R.,Closa, R.,Escribano, J.,Scaglioni, S.,Giovannini, M.,Beyer, J.,Demmelmair, H.,Gruszfeld, D.,Dobrzanska, A.,Sengier, A.,Langhendries, J. P.,Rolland Cachera, M. F.,Grote, V. Lower protein in infant formula is associated with lower weight up to age 2 y: a randomized clinical trial. Am J Clin Nutr.2009;89:1836-45. | IV
322 | Koletzko, B. Complementary foods and the development of food allergy. Pediatrics.2000;106:1285. | Design
323 | Konstantynowicz, J.,Nguyen, T. V.,Kaczmarski, M.,Jamiolkowski, J.,Piotrowska-Jastrzebska, J.,Seeman, E. Fractures during growth: potential role of a milk-free diet. Osteoporos Int.2007;18:1601-7. | Age
324 | Kramer, M. S.,Fombonne, E.,Matush, L.,Bogdanovich, N.,Dahhou, M.,Platt, R. W. Long-term behavioural consequences of infant feeding: the limits of observational studies. Paediatr Perinat Epidemiol.2011;25:500-6. | IV
325 | Kramer, M. S.,Guo, T.,Platt, R. W.,Shapiro, S.,Collet, J. P.,Chalmers, B.,Hodnett, E.,Sevkovskaya, Z.,Dzikovich, I.,Vanilovich, I. Breastfeeding and infant growth: biology or bias?. Pediatrics.2002;110:343-7. | IV
326 | Kramer, M. S.,Moodie, E. E.,Dahhou, M.,Platt, R. W. Breastfeeding and infant size: evidence of reverse causality. Am J Epidemiol.2011;173:978-83. | IV, DV
327 | Kramer, M. S.,Moodie, E. E.,Platt, R. W. Infant feeding and growth: can we answer the causal question?. Epidemiology.2012;23:790-4. | Design
328 | Kramer, M. S. Do breast-feeding and delayed introduction of solid foods protect against subsequent obesity?. J Pediatr.1981;98:883-7. | Design
329 | Krebs,N. F. Culbertson D. L. Westcott J. L. Sherlock L. Hambidge K. M. Normal Iron Status in Breastfed Infants Consuming Meat as an Early Complementary Food. Pediatric Academic Societies Annual Meeting.2011. | Design
330 | Krebs,N. F.,Hambidge,K. M.,Westcott,J. E.,Miller,L. V.,Sian,L.,Bell,M.,Grunwald,G. Exchangeable zinc pool size in infants is related to key variables of zinc homeostasis. J Nutr.2003;133:1498s-501s. | DV
331 | Krebs,N. F.,Mazariegos,M.,Chomba,E.,Sami,N.,Pasha,O.,Tshefu,A.,Carlo,W. A.,Goldenberg,R. L.,Bose,C. L.,Wright,L. L.,Koso-Thomas,M.,Goco,N.,Kindem,M.,McClure,E. M.,Westcott,J.,Garces,A.,Lokangaka,A.,Manasyan,A.,Imenda,E.,Hartwell,T. D.,Hambidge,K. M. Randomized controlled trial of meat compared with multimicronutrient-fortified cereal in infants and toddlers with high stunting rates in diverse settings. Am J Clin Nutr.2012;96:840-7. | Country
332 | Krebs,N. F.,Westcott,J. E.,Culbertson,D. L.,Sian,L.,Miller,L. V.,Hambidge,K. M. Comparison of complementary feeding strategies to meet zinc requirements of older breastfed infants. Am J Clin Nutr.2012;96:30-5. | DV
333 | Kronborg, H.,Foverskov, E.,Vaeth, M. Predictors for early introduction of solid food among Danish mothers and infants: an observational study. BMC Pediatr.2014;14:243. | Design, DV
334 | Kuklina, E. V.,Ramakrishnan, U.,Stein, A. D.,Barnhart, H. H.,Martorell, R. Growth and diet quality are associated with the attainment of walking in rural Guatemalan infants. J Nutr.2004;134:3296-300. | IV
335 | Kumar, V.,Sharma, S.,Khanna, P.,Vanaja, K. Breast vs bottle feeding-impact on growth in urban infants. Indian J Pediatr.1981;48:271-5. | IV, DV
336 | Kusin, J. A.,Kardjati, S.,van Steenbergen, W. M.,Renqvist, U. H. Nutritional transition during infancy in East Java, Indonesia: 2. A longitudinal study of growth in relation to the intake of breast milk and additional foods. Eur J Clin Nutr.1991;45:77-84. | IV
337 | Kusin, J. A.,Kardjati, S.,van Steenbergen, W. Traditional infant feeding practices: right or wrong?. Soc Sci Med.1985;21:283-6. | IV, Country
338 | Kwok, M. K.,Leung, G. M.,Lam, T. H.,Schooling, C. M. Breastfeeding, childhood milk consumption, and onset of puberty. Pediatrics.2012;130:e631-9. | DV
339 | Laitinen,K.,Kalliomaki,M.,Poussa,T.,Lagstrom,H.,Isolauri,E. Evaluation of diet and growth in children with and without atopic eczema: follow-up study from birth to 4 years. Br J Nutr.2005;94:565-74. | IV, DV
340 | Lampe,J. B.,Velez,N. The effect of prolonged bottle feeding on cow’s milk intake and iron stores at 18 months of age. Clin Pediatr (Phila).1997;36:569-72. | Design
341 | Lang B,Moynihan P. The weaning diet: promoting growth while safeguarding dental health. Quintessence Int.2006;37:632-6. | Design
342 | Larnkjaer, A.,Hoppe, C.,Molgaard, C.,Michaelsen, K. F. The effects of whole milk and infant formula on growth and IGF-I in late infancy. Eur J Clin Nutr.2009;63:956-63. | IV
343 | Lasky, P. A.,Eichelberger, K. M. Implications, considerations, and nursing interventions of obesity in neonatal and preschool patients. Nurs Clin North Am.1982;17:199-205. | Design
344 | Lauzon-Guillain, Bd,Wijndaele, K.,Clark, M.,Acerini, C. L.,Hughes, I. A.,Dunger, D. B.,Wells, J. C.,Ong, K. K. Breastfeeding and infant temperament at age three months. PLoS One.2012;7:e29326. | Design, IV
345 | Lawlor, D. A.,Riddoch, C. J.,Page, A. S.,Andersen, L. B.,Wedderkopp, N.,Harro, M.,Stansbie, D.,Smith, G. D. Infant feeding and components of the metabolic syndrome: findings from the European Youth Heart Study. Arch Dis Child.2005;90:582-8. | IV
346 | Lee, K. Crying and behavior pattern in breast- and formula-fed infants. Early Hum Dev.2000;58:133-40. | Design, IV, DV
347 | Leermakers, E. T.,Kiefte-de Jong, J. C.,Hofman, A.,Jaddoe, V. W.,Franco, O. H. Lutein intake at the age of 1 year and cardiometabolic health at the age of 6 years: the Generation R Study. Br J Nutr.2015;114:970-8. | IV
348 | Legovic, M.,Ostric, L. The effects of feeding methods on the growth of the jaws in infants. ASDC J Dent Child.1991;58:253-5. | Design, IV, DV
349 | Lei, D. L.,Chaves, S. P.,Paes, A. T.,Escuder, M. M.,Ribeiro, A. B.,Freire, R. D.,Lerner, B. R. Risk of linear growth retardation during the first two years of life: a new approach. Eur J Clin Nutr.1999;53:456-60. | IV
350 | Leonard, W. R.,Dewalt, K. M.,Stansbury, J. P.,McCaston, M. K. Influence of dietary quality on the growth of highland and coastal Ecuadorian children. Am J Hum Biol.2000;12:825-837. | IV
351 | Leroy, J. L.,Ruel, M.,Habicht, J. P.,Frongillo, E. A. Using height-for-age differences (HAD) instead of height-for-age z-scores (HAZ) for the meaningful measurement of population-level catch-up in linear growth in children less than 5 years of age. BMC Pediatr.2015;15:145. | IV
352 | Leung, S. S.,Peng, C. X.,Xu, Y. Y.,Liu, K. M.,Quan, X. J.,Lui, S.,Davies, D. P. Comparative study of growth of Chinese infants: Hong Kong versus Guangzhou. J Trop Pediatr.1994;40:166-71. | IV, DV
353 | Leung,S.,Davies,D. P. Infant feeding and growth of Chinese infants: birth to 2 years. Paediatr Perinat Epidemiol.1994;8:301-13. | IV, DV
354 | Leventakou, V.,Roumeliotaki, T.,Koutra, K.,Vassilaki, M.,Mantzouranis, E.,Bitsios, P.,Kogevinas, M.,Chatzi, L. Breastfeeding duration and cognitive, language and motor development at 18 months of age: Rhea mother-child cohort in Crete, Greece. J Epidemiol Community Health.2015;69:232-9. | IV
355 | Li, C.,Kaur, H.,Choi, W. S.,Huang, T. T.,Lee, R. E.,Ahluwalia, J. S. Additive interactions of maternal prepregnancy BMI and breast-feeding on childhood overweight. Obes Res.2005;13:362-71. | IV
356 | Li, R.,Magadia, J.,Fein, S. B.,Grummer-Strawn, L. M. Risk of bottle-feeding for rapid weight gain during the first year of life. Arch Pediatr Adolesc Med.2012;166:431-6. | IV
357 | Lin, S. L.,Leung, G. M.,Lam, T. H.,Schooling, C. M. Timing of solid food introduction and obesity: Hong Kong’s “children of 1997” birth cohort. Pediatrics.2013;131:e1459-67. | Design
358 | Lind,T.,Lonnerdal,B.,Persson,L. A.,Stenlund,H.,Tennefors,C.,Hernell,O. Effects of weaning cereals with different phytate contents on hemoglobin, iron stores, and serum zinc: a randomized intervention in infants from 6 to 12 mo of age. Am J Clin Nutr.2003;78:168-75. | DV
359 | Livingstone V. Failure to thrive while breastfeeding. Breastfeed Med.2006;1:108-11. | Design
360 | Lozoff, B.,De Andraca, I.,Castillo, M.,Smith, J. B.,Walter, T.,Pino, P. Behavioral and developmental effects of preventing iron-deficiency anemia in healthy full-term infants. Pediatrics.2003;112:846-54. | IV
361 | Lucas, R.,Judge, M.,Sajdlowska, J.,Cong, X.,McGrath, J. M.,Brandon, D. Effect of Maternal Body Mass Index on Infant Breastfeeding Behaviors and Exclusive Direct Breastfeeding. J Obstet Gynecol Neonatal Nurs.2015;44:772-83. | DV
362 | Lutter, C. K.,Mora, J. O.,Habicht, J. P.,Rasmussen, K. M.,Robson, D. S.,Herrera, M. G. Age-specific responsiveness of weight and length to nutritional supplementation. Am J Clin Nutr.1990;51:359-64. | IV
363 | Lutter, C. K.,Mora, J. O.,Habicht, J. P.,Rasmussen, K. M.,Robson, D. S.,Sellers, S. G.,Super, C. M.,Herrera, M. G. Nutritional supplementation: effects on child stunting because of diarrhea. Am J Clin Nutr.1989;50:1-8. | IV
364 | Lutter,C. K.,Rodriguez,A.,Fuenmayor,G.,Avila,L.,Sempertegui,F.,Escobar,J. Growth and micronutrient status in children receiving a fortified complementary food. J Nutr.2008;138:379-88. | IV
365 | Luukkainen,P.,Salo,M. K.,Visakorpi,J. K.,Raiha,N. C.,Nikkari,T. Impact of solid food on plasma arachidonic and docosahexaenoic acid status of term infants at 8 months of age. J Pediatr Gastroenterol Nutr.1996;23:229-34. | IV, DV
366 | MacCarthy, D. Psychological influences affecting growth. Health Visit.1980;53:470-6. | Design
367 | Magarey, A.,Kavian, F.,Scott, J. A.,Markow, K.,Daniels, L. Feeding Mode of Australian Infants in the First 12 Months of Life: An Assessment against National Breastfeeding Indicators. J Hum Lact.2015. | DV
368 | Maimaitiming, T.,Wang, Y. P. Feeding and intellectual development in infants and children from Uygur, Kazak, and Han nationality: A comparison of 454 cases. Journal of Clinical Rehabilitative Tissue Engineering Research.2007;11:10710-10712. | Design
369 | Makrides,M.,Gould,J. F.,Gawlik,N. R.,Yelland,L. N.,Smithers,L. G.,Anderson,P. J.,Gibson,R. A. Four-year follow-up of children born to women in a randomized trial of prenatal DHA supplementation. Jama.2014;311:1802-4. | IV
370 | Male,C.,Persson,L. A.,Freeman,V.,Guerra,A.,van’t Hof,M. A.,Haschke,F. Prevalence of iron deficiency in 12-mo-old infants from 11 European areas and influence of dietary factors on iron status (Euro-Growth study). Acta Paediatr.2001;90:492-8. | DV
371 | Mallan, K. M.,Fildes, A.,Magarey, A. M.,Daniels, L. A. The Relationship between Number of Fruits, Vegetables, and Noncore Foods Tried at Age 14 Months and Food Preferences, Dietary Intake Patterns, Fussy Eating Behavior, and Weight Status at Age 3.7 Years. J Acad Nutr Diet.2016;116:630-7. | DV
372 | Mallard,S. R.,Houghton,L. A.,Filteau,S.,Mullen,A.,Nieuwelink,J.,Chisenga,M.,Siame,J.,Gibson,R. S. Dietary diversity at 6 months of age is associated with subsequent growth and mediates the effect of maternal education on infant growth in urban Zambia. J Nutr.2014;144:1818-25. | Country
373 | Mamabolo, R. L.,Alberts, M.,Mbenyane, G. X.,Steyn, N. P.,Nthangeni, N. G.,Delemarre-Van De Waal, H. A.,Levitt, N. S. Feeding practices and growth of infants from birth to 12 months in the central region of the Limpopo Province of South Africa. Nutrition.2004;20:327-33. | IV, DV
374 | Mamabolo,R. L.,Alberts,M.,Levitt,N. S.,Delemarre-van de Waal,H. A.,Steyn,N. P. Association between insulin-like growth factor-1, insulin-like growth factor-binding protein-1 and leptin levels with nutritional status in 1-3-year-old children, residing in the central region of Limpopo Province, South Africa. Br J Nutr.2007;98:762-9. | IV
375 | Mamun, A. A.,Lawlor, D. A.,O’Callaghan, M. J.,Williams, G. M.,Najman, J. M. Family and early life factors associated with changes in overweight status between ages 5 and 14 years: findings from the Mater University Study of Pregnancy and its outcomes. Int J Obes (Lond).2005;29:475-82. | IV
376 | Manjrekar, C.,Vishalakshi, M. P.,Begum, N. J.,Padma, G. N. Breast feeding ability of undernourished mothers and physical development of their infants during 0-1 year. Indian Pediatr.1985;22:801-9. | IV, DV
377 | Marques,R. C.,Dorea,J. G.,Bernardi,J. V.,Bastos,W. R.,Malm,O. Maternal fish consumption in the nutrition transition of the Amazon Basin: growth of exclusively breastfed infants during the first 5 years. Ann Hum Biol.2008;35:363-77. | IV
378 | Marquis, G. S.,Habicht, J. P.,Lanata, C. F.,Black, R. E.,Rasmussen, K. M. Association of breastfeeding and stunting in Peruvian toddlers: an example of reverse causality. Int J Epidemiol.1997;26:349-56. | Design
379 | Marquis, G. S.,Habicht, J. P.,Lanata, C. F.,Black, R. E.,Rasmussen, K. M. Breast milk or animal-product foods improve linear growth of Peruvian toddlers consuming marginal diets. Am J Clin Nutr.1997;66:1102-9. | Design
380 | Martin, R. M.,McCarthy, A.,Smith, G. D.,Davies, D. P.,Ben-Shlomo, Y. Infant nutrition and blood pressure in early adulthood: the Barry Caerphilly Growth study. Am J Clin Nutr.2003;77:1489-97. | IV, DV
381 | Martin, R. M.,Smith, G. D.,Mangtani, P.,Frankel, S.,Gunnell, D. Association between breast feeding and growth: the Boyd-Orr cohort study. Arch Dis Child Fetal Neonatal Ed.2002;87:F193-201. | IV
382 | Martines, J. C.,Habicht, J. P.,Ashworth, A.,Kirkwood, B. R. Weaning in southern Brazil: is there a “weanling’s dilemma”?. J Nutr.1994;124:1189-98. | IV
383 | Matsuzaki,M.,Kuper,H.,Kulkarni,B.,Radhakrishna,K. V.,Viljakainen,H.,Taylor,A. E.,Sullivan,R.,Bowen,L.,Tobias,J. H.,Ploubidis,G. B.,Wells,J. C.,Prabhakaran,D.,Smith,G. D.,Ebrahim,S.,Ben-Shlomo,Y.,Kinra,S. Life-course determinants of bone mass in young adults from a transitional rural community in India: The Andhra Pradesh Children and Parents Study (APCAPS). American Journal of Clinical Nutrition.2014;99:1450-1459. | Design, IV, Age
384 | May, A. L.,Dietz, W. H. The Feeding Infants and Toddlers Study 2008: opportunities to assess parental, cultural, and environmental influences on dietary behaviors and obesity prevention among young children. J Am Diet Assoc.2010;110:S11-5. | Design
385 | Mazariegos,M.,Hambidge,K. M.,Westcott,J. E.,Solomons,N. W.,Raboy,V.,Das,A.,Goco,N.,Kindem,M.,Wright,L. L.,Krebs,N. F. Neither a zinc supplement nor phytate-reduced maize nor their combination enhance growth of 6- to 12-month-old Guatemalan infants. J Nutr.2010;140:1041-8. | Country
386 | McGuire, E. Breastfeeding and high maternal body mass index. Breastfeed Rev.2013;21:7-14. | Design
387 | McNeill, G. Birth weight, feeding practices and weight-for-age of Punjabi children in the UK and in the rural Punjab. Hum Nutr Clin Nutr.1985;39:69-72. | Design
388 | Mehta KC,Specker BL,Bartholmey S,Giddens J,Ho ML. Trial on timing of introduction to solids and food type on infant growth. Pediatrics.1998;102:569-73. | IV
389 | Mei, H.,Guo, B.,Yin, B.,Liang, X.,Adair, L.,Thompson, A.,Zhang, J. Interactive Effects of Early Exclusive Breastfeeding and Pre-Pregnancy Maternal Weight Status on Young Children’s BMI - A Chinese Birth Cohort. PLoS One.2015;10:e0144357. | IV
390 | Meldrum,S. J.,D’Vaz,N.,Simmer,K.,Dunstan,J. A.,Hird,K.,Prescott,S. L. Effects of high-dose fish oil supplementation during early infancy on neurodevelopment and language: a randomised controlled trial. Br J Nutr.2012;108:1443-54. | IV
391 | Melnik, B. Growth and puberty in German children: is there still a positive secular trend? Consumption of milk as a vital factor in growth development..Bettina Gohlke, Woelfle JF. volume 23/2009. Deutsches Aerzteblatt International.2009;106:656-656. | Design
392 | Mennella, J. A.,Castor, S. M. Sensitive period in flavor learning: effects of duration of exposure to formula flavors on food likes during infancy. Clin Nutr.2012;31:1022-5. | DV
393 | Merten, S.,Dratva, J.,Ackermann-Liebrich, U. Do baby-friendly hospitals influence breastfeeding duration on a national level?. Pediatrics.2005;116:e702-8. | Design, IV
394 | Michaelsen, K. F.,Johansen, J. S.,Samuelson, G.,Price, P. A.,Christiansen, C. Serum bone gamma-carboxyglutamic acid protein in a longitudinal study of infants: lower values in formula-fed infants. Pediatr Res.1992;31:401-5. | IV
395 | Michaelsen, K. F. Are there negative effects of an excessive protein intake?. Pediatrics.2000;106:1293. | Design
396 | Michaelsen,K. F.,Milman,N.,Samuelson,G. A longitudinal study of iron status in healthy Danish infants: effects of early iron status, growth velocity and dietary factors. Acta Paediatr.1995;84:1035-44. | IV, DV
397 | Michaelsen,K. F. Cows’ milk in complementary feeding. Pediatrics.2000;106:1302-3. | Design
398 | Michaelsen,K. F. Nutrition and growth during infancy. The Copenhagen Cohort Study. Acta Paediatr Suppl.1997;420:1-36. | Design, IV
399 | Michels, K. B.,Willett, W. C.,Graubard, B. I.,Vaidya, R. L.,Cantwell, M. M.,Sansbury, L. B.,Forman, M. R. A longitudinal study of infant feeding and obesity throughout life course. Int J Obes (Lond).2007;31:1078-85. | IV
400 | Mihrshahi, S.,Battistutta, D.,Magarey, A.,Daniels, L. A. Determinants of rapid weight gain during infancy: baseline results from the NOURISH randomised controlled trial. BMC Pediatr.2011;11:99. | Design
401 | Millar, L.,Kremer, P.,de Silva-Sanigorski, A.,McCabe, M. P.,Mavoa, H.,Moodie, M.,Utter, J.,Bell, C.,Malakellis, M.,Mathews, L.,Roberts, G.,Robertson, N.,Swinburn, B. A. Reduction in overweight and obesity from a 3-year community-based intervention in Australia: the ‘It’s Your Move!’ project. Obes Rev.2011;12 Suppl 2:20-8. | IV, Age
402 | Mimouni-Bloch, A.,Kachevanskaya, A.,Mimouni, F. B.,Shuper, A.,Raveh, E.,Linder, N. Breastfeeding may protect from developing attention-deficit/hyperactivity disorder. Breastfeed Med.2013;8:363-7. | IV
403 | Mittal, S.,Gupta, M. C. Evaluation of a supplementary feeding programme through take home system. J Trop Pediatr.1980;26:50-3. | IV
404 | Miura T,Fukuda M,Mizuno M,Ohte N. Need for public awareness regarding low birth weight and bottle feeding. Hypertens Res.2016. | Design
405 | Molgaard, C.,Larnkjaer, A.,Mark, A. B.,Michaelsen, K. F. Are early growth and nutrition related to bone health in adolescence? The Copenhagen Cohort Study of infant nutrition and growth. Am J Clin Nutr.2011;94:1865s-1869s. | IV
406 | Moller, L. M.,de Hoog, M. L.,van Eijsden, M.,Gemke, R. J.,Vrijkotte, T. G. Infant nutrition in relation to eating behaviour and fruit and vegetable intake at age 5 years. Br J Nutr.2013;109:564-71. | DV
407 | Monterrosa EC,Frongillo EA,Neufeld LM,Egan KA,Ramakrishnan U,Rasmussen KM. Maternal pre-pregnancy body mass index is not associated with infant and young child feeding in low-income Mexican children 1-24 months old. Matern Child Nutr.2015;11:215-28. | DV
408 | Monterrosa,E. C.,Frongillo,E. A.,Vasquez-Garibay,E. M.,Romero-Velarde,E.,Casey,L. M.,Willows,N. D. Predominant breast-feeding from birth to six months is associated with fewer gastrointestinal infections and increased risk for iron deficiency among infants. J Nutr.2008;138:1499-504. | IV
409 | Monti G,Viola S,Baro C,Cresi F,Tovo PA,Moro G,Ferrero MP,Conti A,Bertino E. Tolerability of donkey’s milk in 92 highly-problematic cow’s milk allergic children. J Biol Regul Homeost Agents.2012;26:75-82. | IV
410 | Moore,S. E.,Prentice,A. M.,Wagatsuma,Y.,Fulford,A. J.,Collinson,A. C.,Raqib,R.,Vahter,M.,Persson,L. A.,Arifeen,S. E. Early-life nutritional and environmental determinants of thymic size in infants born in rural Bangladesh. Acta Paediatr.2009;98:1168-75. | IV, DV
411 | Moreno M. Early infant feeding and obesity risk. JAMA Pediatr.2014;168:1084. | Design
412 | Morgan JB,Mumford PM. A follow-up study of nutrition and anthropometry in pre-school children. Proc Nutr Soc.1980;39:5a. | Design
413 | Morgan, J. B.,Lucas, A.,Fewtrell, M. S. Does weaning influence growth and health up to 18 months?. Archives of Disease in Childhood: Education and Practice Edition.2004;89:728-733. | Design
414 | Morley,R.,Abbott,R.,Fairweather-Tait,S.,MacFadyen,U.,Stephenson,T.,Lucas,A. Iron fortified follow on formula from 9 to 18 months improves iron status but not development or growth: a randomised trial. Arch Dis Child.1999;81:247-52. | IV
415 | Morrow-Tlucak, M.,Haude, R. H.,Ernhart, C. B. Breastfeeding and cognitive development in the first 2 years of life. Soc Sci Med.1988;26:635-9. | IV
416 | Morton,R. E.,Nysenbaum,A.,Price,K. Iron status in the first year of life. J Pediatr Gastroenterol Nutr.1988;7:707-12. | DV
417 | Mumford, P.,Morgan, J. B. A longitudinal study of nutrition and growth of infants initially on the upper and lower centile for weight and age. Int J Obes.1982;6:335-41. | IV, DV
418 | Musaad, S. M.,Donovan, S. M.,Fiese, B. H. Parental perception of child weight in the first two years-of-life: a potential link between infant feeding and preschoolers’ diet. Appetite.2015;91:90-100. | Design, DV
419 | Nagahara, K.,Dobashi, K.,Itabashi, K. Feeding choice has a gender-associated effect on infant growth. Pediatr Int.2013;55:481-7. | IV
420 | Nakao, R. M. Effects of an education program on the health and illness profile of rural breast-fed babies. Philipp J Nurs.1988;58:12-8. | IV
421 | Narese, F.,Puccio, G.,Mazzucco, W.,Falzone, A.,Venturella, V.,Narese, D.,Capra, E. Earlier appearance of the ossification center of the femoral head in breast-fed versus formula-fed infants. Nutrition.2011;27:1108-11. | Design, IV
422 | Nauta,A. J.,Garssen,J. Nutritional programming of immune defense against infections in early life. Nutricia Research, Utrecht, Netherlands.2014;12:113-126. | Design
423 | Newman,J. E.,Garces,A.,Mazariegos,M.,Michael Hambidge,K.,Manasyan,A.,Tshefu,A.,Lokangaka,A.,Sami,N.,Carlo,W. A.,Bose,C. L.,Pasha,O.,Goco,N.,Chomba,E.,Goldenberg,R. L.,Wright,L. L.,Koso-Thomas,M.,Krebs,N. F. Theory-driven process evaluation of a complementary feeding trial in four countries. Health Educ Res.2014;29:297-305. | Design, DV
424 | Ng, S. C.,Chong, Y. S.,Rauff, M.,Myo, Z. M.,Nurfarah, C.,Deurenberg, P. R. The influence of breast feeding compared to formula feeding on infant adiposity. Ann Acad Med Singapore.2004;33:S75. | Design, IV
425 | Nguyen, N. D.,Allen, J. R.,Peat, J. K.,Schofield, W. N.,Nossar, V.,Eisenbruch, M.,Gaskin, K. J. Growth and feeding practices of Vietnamese infants in Australia. Eur J Clin Nutr.2004;58:356-62. | IV, DV
426 | Nielsen GA,Thomsen BL,Michaelsen KF. Influence of breastfeeding and complementary food on growth between 5 and 10 months. Acta Paediatr.1998;87:911-7. | Design
427 | Niinikoski, H.,Lagstrom, H.,Jokinen, E.,Siltala, M.,Ronnemaa, T.,Viikari, J.,Raitakari, O. T.,Jula, A.,Marniemi, J.,Nanto-Salonen, K.,Simell, O. Impact of repeated dietary counseling between infancy and 14 years of age on dietary intakes and serum lipids and lipoproteins: the STRIP study. Circulation.2007;116:1032-40. | IV
428 | Northstone, K.,Emmett, P.,Nethersole, F. The effect of age of introduction to lumpy solids on foods eaten and reported feeding difficulties at 6 and 15 months. J Hum Nutr Diet.2001;14:43-54. | DV
429 | Novotny, R.,Coleman, P.,Tenorio, L.,Davison, N.,Camacho, T.,Ramirez, V.,Vijayadeva, V.,Untalan, P.,Tudela, M. D. Breastfeeding is associated with lower body mass index among children of the Commonwealth of the Northern Mariana Islands. J Am Diet Assoc.2007;107:1743-6. | Design, IV
430 | Ntouva, A.,Rogers, I.,MacAdam, A.,Emmett, P. Weaning practices and iron status of exclusively breast fed infants. Journal of Human Nutrition & Dietetics.2011;24:297-298 2p. | Design
431 | Nwaru BI,Takkinen HM,Niemela O,Kaila M,Erkkola M,Ahonen S,Haapala AM,Kenward MG,Pekkanen J,Lahesmaa R,Kere J,Simell O,Veijola R,Ilonen J,Hyoty H,Knip M,Virtanen SM. Timing of infant feeding in relation to childhood asthma and allergic diseases. J Allergy Clin Immunol.2013;131:78-86. | DV
432 | Obatolu, V. A. Growth pattern of infants fed with a mixture of extruded malted maize and cowpea. Nutrition.2003;19:174-8. | Country
433 | Oddy, W. H.,Kendall, G. E.,Blair, E.,De Klerk, N. H.,Stanley, F. J.,Landau, L. I.,Silburn, S.,Zubrick, S. Breast feeding and cognitive development in childhood: a prospective birth cohort study. Paediatr Perinat Epidemiol.2003;17:81-90. | IV
434 | Oddy, W. H.,Robinson, M.,Kendall, G. E.,Li, J.,Zubrick, S. R.,Stanley, F. J. Breastfeeding and early child development: a prospective cohort study. Acta Paediatr.2011;100:992-9. | IV
435 | Oddy, W. H.,Sherriff, J. L. Breastfeeding, body mass index, asthma and atopy in children. Asia Pac J Public Health.2003;15 Suppl:S15-7. | IV
436 | O’Donovan,S. M.,O’B Hourihane J,Murray,D. M.,Kenny,L. C.,Khashan,A. S.,Chaoimh,C. N.,Irvine,A. D.,Kiely,M. Neonatal adiposity increases the risk of atopic dermatitis during the first year of life. J Allergy Clin Immunol.2015. | DV
437 | Oelofse,A.,Van Raaij,J. M.,Benade,A. J.,Dhansay,M. A.,Tolboom,J. J.,Hautvast,J. G. The effect of a micronutrient-fortified complementary food on micronutrient status, growth and development of 6- to 12-month-old disadvantaged urban South African infants. Int J Food Sci Nutr.2003;54:399-407. | Country
438 | Ong, K. K.,Emmett, P. M.,Noble, S.,Ness, A.,Dunger, D. B. Dietary energy intake at the age of 4 months predicts postnatal weight gain and childhood body mass index. Pediatrics.2006;117:e503-8. | IV
439 | Ong, K. K.,Preece, M. A.,Emmett, P. M.,Ahmed, M. L.,Dunger, D. B. Size at birth and early childhood growth in relation to maternal smoking, parity and infant breast-feeding: longitudinal birth cohort study and analysis. Pediatr Res.2002;52:863-7. | IV
440 | Onyango, A. W.,Borghi, E.,de Onis, M.,Casanovas Mdel, C.,Garza, C. Complementary feeding and attained linear growth among 6-23-month-old children. Public Health Nutr.2014;17:1975-83. | Design
441 | Ou, X.,Andres, A.,Cleves, M. A.,Pivik, R. T.,Snow, J. H.,Ding, Z.,Badger, T. M. Sex-specific association between infant diet and white matter integrity in 8-y-old children. Pediatr Res.2014;76:535-43. | IV
442 | Ounsted, M. K.,Moar, V. A.,Scott, A. Large-for-dates babies at the age of four years: health, handicap and developmental status. Early Hum Dev.1983;9:9-19. | IV
443 | Pachucki MA. Food pattern analysis over time: unhealthful eating trajectories predict obesity. Int J Obes (Lond).2012;36:686-94. | Age
444 | Parry, J. E.,Ip, D. K.,Chau, P. Y.,Wu, K. M.,Tarrant, M. Predictors and consequences of in-hospital formula supplementation for healthy breastfeeding newborns. J Hum Lact.2013;29:527-36. | IV, DV
445 | Parsons, T. J.,Power, C.,Manor, O. Infant feeding and obesity through the lifecourse. Arch Dis Child.2003;88:793-4. | IV
446 | Patsourou, A.,Konstantinides, T.,Mantadakis, E.,Tsalkidis, A.,Zarras, C.,Balaska, A.,Simopoulos, K.,Chatzimichael, A. Growth of exclusively breastfed and self-weaned children of Greece aged 0-36 months. Breastfeed Med.2012;7:521-5. | IV
447 | Paul IM,Savage JS,Anzman SL,Beiler JS,Marini ME,Stokes JL,Birch LL. Preventing obesity during infancy: a pilot study. Obesity (Silver Spring).2011;19:353-61. | IV
448 | Paul, A.,Whitehead, R. Infant feeding: the weighting game. Community Outlook.1986:11-7. | Design
449 | Paul, S. P.,Smith, B. A.,Taylor, T. M.,Walker, J. Take with a grain of salt. Clin Chem.2013;59:348-51. | Design
450 | Peat,J. K.,Mihrshahi,S.,Kemp,A. S.,Marks,G. B.,Tovey,E. R.,Webb,K.,Mellis,C. M.,Leeder,S. R. Three-year outcomes of dietary fatty acid modification and house dust mite reduction in the Childhood Asthma Prevention Study. J Allergy Clin Immunol.2004;114:807-13. | IV, DV
451 | Penny,M. E.,Creed-Kanashiro,H. M.,Robert,R. C.,Narro,M. R.,Caulfield,L. E.,Black,R. E. Effectiveness of an educational intervention delivered through the health services to improve nutrition in young children: a cluster-randomised controlled trial. Lancet.2005;365:1863-72. | IV
452 | Penrod,J. C.,Anderson,K.,Acosta,P. B. Impact on iron status of introducing cow’s milk in the second six months of life. J Pediatr Gastroenterol Nutr.1990;10:462-7. | IV, DV
453 | Perez-Escamilla, R.,Cohen, R. J.,Brown, K. H.,Rivera, L. L.,Canahuati, J.,Dewey, K. G. Maternal anthropometric status and lactation performance in a low-income Honduran population: evidence for the role of infants. Am J Clin Nutr.1995;61:528-34. | IV, DV
454 | Persson LA. Infant feeding and growth--a longitudinal study in three Swedish communities. Ann Hum Biol.1985;12:41-52. | IV
455 | Persson,L. A.,Lundstrom,M.,Lonnerdal,B.,Hernell,O. Are weaning foods causing impaired iron and zinc status in 1-year-old Swedish infants? A cohort study. Acta Paediatr.1998;87:618-22. | IV, DV
456 | Peters,R. L.,Allen,K. J.,Dharmage,S. C.,Lodge,C. J.,Koplin,J. J.,Ponsonby,A. L.,Wake,M.,Lowe,A. J.,Tang,M. L.,Matheson,M. C.,Gurrin,L. C. Differential factors associated with challenge-proven food allergy phenotypes in a population cohort of infants: a latent class analysis. Clin Exp Allergy.2015;45:953-63. | DV
457 | Pfluger M,Winkler C,Hummel S,Ziegler AG. Early infant diet in children at high risk for type 1 diabetes. Horm Metab Res.2010;42:143-8. | IV
458 | Pham,V. P.,Nguyen,V. H.,Salvignol,B.,Treche,S.,Wieringa,F. T.,Dijkhuizen,M. A.,Nguyen,C. K.,Pham,D. T.,Schwartz,H.,Berger,J. A six-month intervention with two different types of micronutrient-fortified complementary foods had distinct short- and long-term effects on linear and ponderal growth of Vietnamese infants. J Nutr.2012;142:1735-40. | Country
459 | Phu,P. V.,Hoan,N. V.,Salvignol,B.,Treche,S.,Wieringa,F. T.,Khan,N. C.,Tuong,P. D.,Berger,J. Complementary foods fortified with micronutrients prevent iron deficiency and anemia in Vietnamese infants. J Nutr.2010;140:2241-7. | DV
460 | Piemontese, P.,Gianni, M. L.,Braegger, C. P.,Chirico, G.,Gruber, C.,Riedler, J.,Arslanoglu, S.,van Stuijvenberg, M.,Boehm, G.,Jelinek, J.,Roggero, P. Tolerance and safety evaluation in a large cohort of healthy infants fed an innovative prebiotic formula: a randomized controlled trial. PLoS One.2011;6:e28010. | IV
461 | Pimpin, L.,Jebb, S.,Johnson, L.,Wardle, J.,Ambrosini, G. L. Dietary protein intake is associated with body mass index and weight up to 5 y of age in a prospective cohort of twins. Am J Clin Nutr.2016;103:389-97. | IV
462 | Pivik, R. T.,Andres, A.,Badger, T. M. Effects of diet on early stage cortical perception and discrimination of syllables differing in voice-onset time: a longitudinal ERP study in 3 and 6 month old infants. Brain Lang.2012;120:27-41. | IV
463 | Pivik, R. T.,Dykman, R. A.,Jing, H.,Gilchrist, J. M.,Badger, T. M. The influence of infant diet on early developmental changes in processing human voice speech stimuli: ERP variations in breast and milk formula-fed infants at 3 and 6 months after birth. Dev Neuropsychol.2007;31:279-335. | IV
464 | Piwoz, E. G.,Black, R. E.,Lopez de Romana, G.,Creed de Kanashiro, H.,Brown, K. H. The relationship between infants’ preceding appetite, illness, and growth performance and mothers’ subsequent feeding practice decisions. Soc Sci Med.1994;39:851-60. | IV, DV
465 | Piwoz, E. G.,Creed de Kanashiro, H.,Lopez de Romana, G.,Black, R. E.,Brown, K. H. Within- and between-individual variation in energy intakes by low-income Peruvian infants. Eur J Clin Nutr.1994;48:333-40. | IV, DV
466 | Piwoz,E. G.,Lopez de Romana,G.,Creed de Kanashiro,H.,Black,R. E.,Brown,K. H. Indicators for monitoring the growth of peruvian infants: weight and length gain vs attained weight and length. Am J Public Health.1994;84:1132-8. | IV
467 | Plagemann, A.,Harder, T.,Kohlhoff, R.,Fahrenkrog, S.,Rodekamp, E.,Franke, K.,Dudenhausen, J. W. Impact of early neonatal breast-feeding on psychomotor and neuropsychological development in children of diabetic mothers. Diabetes Care.2005;28:573-8. | IV
468 | Plonka, K. A.,Pukallus, M. L.,Barnett, A.,Holcombe, T. F.,Walsh, L. J.,Seow, W. K. A controlled, longitudinal study of home visits compared to telephone contacts to prevent early childhood caries. Int J Paediatr Dent.2013;23:23-31. | DV
469 | Poh,Bee Koon,Ng,Boon Koon,Siti Haslinda,Mohd Din,Nik Shanita,Safii,Wong,Jyh Eiin,Budin,Siti Balkis,Ruzita,Abd Talib,Ng,Lai Oon,Khouw,Ilse,Norimah,A. Karim. Nutritional status and dietary intakes of children aged 6 months to 12 years: findings of the Nutrition Survey of Malaysian Children (SEANUTS Malaysia). British Journal of Nutrition.2013;110:S21-35 1p. | Design, IV
470 | Polańska, K.,Muszyński, P.,Sobala, W.,Dziewirska, E.,Merecz-Kot, D.,Hanke, W. Maternal lifestyle during pregnancy and child psychomotor development - Polish Mother and Child Cohort study. Early Human Development.2015;91:317-325. | IV
471 | Pollitt, E.,Gorman, K. S.,Engle, P. L.,Rivera, J. A.,Martorell, R. Nutrition in early life and the fulfillment of intellectual potential. J Nutr.1995;125:1111s-1118s. | Design, IV
472 | Pollitt, E.,Watkins, W. E.,Husaini, M. A. Three-month nutritional supplementation in Indonesian infants and toddlers benefits memory function 8 y later. Am J Clin Nutr.1997;66:1357-63. | Country
473 | Potur, A. H.,Kalmaz, N. An investigation into feeding errors of 0-4-month-old infants. J Trop Pediatr.1995;41:120-2. | Design, IV,DV
474 | Potur, A. H.,Kalmaz, N. An investigation into feeding errors of 0-4-month-old infants. J Trop Pediatr.1996;42:173-5. | Design, IV,DV
475 | Prentice P,Koulman A,Matthews L,Acerini CL,Ong KK,Dunger DB. Lipidomic analyses, breast- and formula-feeding, and growth in infants. J Pediatr.2015;166:276-81.e6. | IV
476 | Pridham, K. F. Infant feeding and anticipatory care: supporting the adaptation of parents to their new babies. Matern Child Nurs J.1981;10:111-26. | Design
477 | Priego, T.,Sanchez, J.,Pico, C.,Ahrens, W.,Bammann, K.,De Henauw, S.,Fraterman, A.,Iacoviello, L.,Lissner, L.,Molnar, D.,Moreno, L. A.,Siani, A.,Tornaritis, M.,Veidebaum, T.,Palou, A. Influence of breastfeeding on blood-cell transcript-based biomarkers of health in children. Pediatr Obes.2014;9:463-70. | IV
478 | Prodam, F.,Roccio, M.,Trovato, L.,Ricotti, R.,Moia, S.,Giglione, E.,Petri, A.,Walker, G. E.,Bellone, S.,Bona, G. Adiponectin oligomers are similarly distributed in adequate-for-gestational-age obese children irrespective of feeding in their first year. Pediatr Res.2015;77:808-13. | IV, DV
479 | Puri, R.,Chawla, P.,Sharma, M.,Pershad, D. Impact of an on-going supplementary feeding programme on the mental abilities of children. Indian J Pediatr.1984;51:653-7. | IV
480 | Purwestri, R. C.,Scherbaum, V.,Inayati, D. A.,Wirawan, N. N.,Suryantan, J.,Bloem, M. A.,Pangaribuan, R. V.,Stuetz, W.,Hoffmann, V.,Qaim, M.,Biesalski, H. K.,Bellows, A. C. Supplementary feeding with locally-produced Ready-to-Use Food (RUF) for mildly wasted children on Nias Island, Indonesia: comparison of daily and weekly program outcomes. Asia Pac J Clin Nutr.2012;21:374-9. | Health status, IV
481 | Qureshi, B.,Morgan, J. B.,Kimer, A. C.,Donaldson, D.,Dickerson, J. W. Feeding practices and birth weights of infants in Southall, Middlesex. J R Soc Health.1988;108:77-80. | IV, DV
482 | Radhakrishna,K. V.,Hemalatha,R.,Geddam,J. J.,Kumar,P. A.,Balakrishna,N.,Shatrugna,V. Effectiveness of zinc supplementation to full term normal infants: a community based double blind, randomized, controlled, clinical trial. PLoS One.2013;8:e61486. | IV
483 | Ramokolo, V.,Lombard, C.,Chhagan, M.,Engebretsen, I. M.,Doherty, T.,Goga, A. E.,Fadnes, L. T.,Zembe, W.,Jackson, D. J.,Van den Broeck, J. Effects of early feeding on growth velocity and overweight/obesity in a cohort of HIV unexposed South African infants and children. Int Breastfeed J.2015;10:14. | IV
484 | Rao,S.,Rajpathak,V. Breastfeeding and weaning practices in relation to nutritional status of infants. Indian Pediatr.1992;29:1533-9. | IV, DV
485 | Rapley, G. Talking about weaning. Community Pract.2011;84:40-1. | Design
486 | Rask-Nissila,L.,Jokinen,E.,Terho,P.,Tammi,A.,Hakanen,M.,Ronnemaa,T.,Viikari,J.,Seppanen,R.,Valimaki,I.,Helenius,H.,Simell,O. Effects of diet on the neurologic development of children at 5 years of age: the STRIP project. J Pediatr.2002;140:328-33. | IV
487 | Ravelli, A. C.,van der Meulen, J. H.,Osmond, C.,Barker, D. J.,Bleker, O. P. Infant feeding and adult glucose tolerance, lipid profile, blood pressure, and obesity. Arch Dis Child.2000;82:248-52. | IV
488 | Reifsnider, E. Reversing growth deficiency in children: the effect of a community-based intervention. J Pediatr Health Care.1998;12:305-12. | Health status, IV
489 | Requejo,A. M.,Navia,B.,Ortega,R. M.,Lopez-Sobaler,A. M.,Quintas,E.,Gaspar,M. J.,Osorio,O. The age at which meat is first included in the diet affects the incidence of iron deficiency and ferropenic anaemia in a group of pre-school children from Madrid. Int J Vitam Nutr Res.1999;69:127-31. | Design
490 | Richards, M.,Wadsworth, M.,Rahimi-Foroushani, A.,Hardy, R.,Kuh, D.,Paul, A. Infant nutrition and cognitive development in the first offspring of a national UK birth cohort. Dev Med Child Neurol.1998;40:163-7. | IV
491 | Rifas-Shiman SL,Sherry B,Scanlon K,Birch LL,Gillman MW,Taveras EM. Does maternal feeding restriction lead to childhood obesity in a prospective cohort study?. Arch Dis Child.2011;96:265-9. | IV
492 | Rios-Castillo, I.,Cerezo, S.,Corvalan, C.,Martinez, M.,Kain, J. Risk factors during the prenatal period and the first year of life associated with overweight in 7-year-old low-income Chilean children. Matern Child Nutr.2015;11:595-605. | Design
493 | Rivera,J. A.,Habicht,J. P. Effect of supplementary feeding on the prevention of mild-to-moderate wasting in conditions of endemic malnutrition in Guatemala. Bull World Health Organ.2002;80:926-32. | IV
494 | Roberts, D. W. Growth of breast fed and bottle fed infants. N Z Med J.1980;92:45-6. | IV
495 | Robinson, S. M.,Simmonds, S. J.,Jameson, K. A.,Syddall, H. E.,Dennison, E. M.,Cooper, C.,Sayer, A. A. Muscle strength in older community-dwelling men is related to type of milk feeding in infancy. J Gerontol A Biol Sci Med Sci.2012;67:990-6. | IV
496 | Robinson, S.,Ntani, G.,Simmonds, S.,Syddall, H.,Dennison, E.,Sayer, A. A.,Barker, D.,Cooper, C. Type of milk feeding in infancy and health behaviours in adult life: findings from the Hertfordshire Cohort Study. Br J Nutr.2013;109:1114-22. | IV, DV
497 | Rogan, W. J.,Gladen, B. C. Breast-feeding and cognitive development. Early Hum Dev.1993;31:181-93. | IV
498 | Rolland-Cachera,M. F.,Maillot,M.,Deheeger,M.,Souberbielle,J. C.,Peneau,S.,Hercberg,S. Association of nutrition in early life with body fat and serum leptin at adult age. Int J Obes (Lond).2013;37:1116-22. | IV
499 | Rosado,J. L.,Lopez,P.,Garcia,O. P.,Alatorre,J.,Alvarado,C. Effectiveness of the nutritional supplement used in the Mexican Oportunidades programme on growth, anaemia, morbidity and cognitive development in children aged 12-24 months. Public Health Nutr.2011;14:931-7. | IV
500 | Routi, T.,Ronnemaa, T.,Lapinleimu, H.,Salo, P.,Viikari, J.,Leino, A.,Valimaki, I.,Jokinen, E.,Simell, O. Effect of weaning on serum lipoprotein(a) concentration: the STRIP baby study. Pediatr Res.1995;38:522-7. | IV, DV
501 | Rowland, M. G. The “why” and “when” of introducing food to infants: growth in young breast-fed infants and some nutritional implications. Am J Clin Nutr.1985;41:459-63. | Design
502 | Roy, S. K.,Fuchs, G. J.,Mahmud, Z.,Ara, G.,Islam, S.,Shafique, S.,Akter, S. S.,Chakraborty, B. Intensive nutrition education with or without supplementary feeding improves the nutritional status of moderately-malnourished children in Bangladesh. J Health Popul Nutr.2005;23:320-30. | Health status
503 | Rudnicka, A. R.,Owen, C. G.,Richards, M.,Wadsworth, M. E.,Strachan, D. P. Effect of breastfeeding and sociodemographic factors on visual outcome in childhood and adolescence. Am J Clin Nutr.2008;87:1392-9. | IV
504 | Rudy,C. A. Vegetarian diets for children. Pediatr Nurs.1984;10:329-33. | Design
505 | Ruel, M. T.,Rivera, J.,Habicht, J. P.,Martorell, R. Differential response to early nutrition supplementation: long-term effects on height at adolescence. Int J Epidemiol.1995;24:404-12. | IV, Date
506 | Russell, C. G.,Taki, S.,Azadi, L.,Campbell, K. J.,Laws, R.,Elliott, R.,Denney-Wilson, E. A qualitative study of the infant feeding beliefs and behaviours of mothers with low educational attainment. BMC Pediatr.2016;16:69. | DV
507 | Ryan, A. S.,Gussler, J. D. Biocultural factors affecting infant feeding and growth. Med Anthropol.1985;9:93-5. | Design
508 | Rzehak, P.,Sausenthaler, S.,Koletzko, S.,Reinhardt, D.,von Berg, A.,Kramer, U.,Berdel, D.,Bollrath, C.,Grubl, A.,Bauer, C. P.,Wichmann, H. E.,Heinrich, J. Long-term effects of hydrolyzed protein infant formulas on growth--extended follow-up to 10 y of age: results from the German Infant Nutritional Intervention (GINI) study. Am J Clin Nutr.2011;94:1803s-1807s. | IV
509 | Saco-Pollitt, C.,Triana, N.,Harahap, H.,Husaini, M.,Jahari, A. B.,Pollitt, E. The eco-cultural context of the undernourished children in a study on the effects of early supplementary feeding in Indonesia. Eur J Clin Nutr.2000;54 Suppl 2:S11-5. | Design, Health status
510 | Sacrey, L. A.,Karl, J. M.,Whishaw, I. Q. Development of rotational movements, hand shaping, and accuracy in advance and withdrawal for the reach-to-eat movement in human infants aged 6-12 months. Infant Behav Dev.2012;35:543-60. | IV, DV
511 | Saha, K. K.,Frongillo, E. A.,Alam, D. S.,Arifeen, S. E.,Persson, L. A.,Rasmussen, K. M. Appropriate infant feeding practices result in better growth of infants and young children in rural Bangladesh. Am J Clin Nutr.2008;87:1852-9. | IV
512 | Samuel, T. M.,Thomas, T.,Bhat, S.,Kurpad, A. V. Are infants born in baby-friendly hospitals being exclusively breastfed until 6 months of age?. Eur J Clin Nutr.2012;66:459-65. | IV
513 | Saner G,Dagoglu T,Uzkan I,Neyzi O. Promotion of breastfeeding in the postpartum mother. Turk J Pediatr.1985;27:63-8. | IV
514 | Sanger, R. G.,Bystrom, E. B. Breast feeding: does it affect oral facial growth?. Dent Hyg (Chic).1982;56:44-7. | Design
515 | Santos, I. S.,Matijasevich, A.,Assuncao, M. C.,Valle, N. C.,Horta, B. L.,Goncalves, H. D.,Gigante, D. P.,Martines, J. C.,Pelto, G.,Victora, C. G. Promotion of Weight Gain in Early Childhood Does Not Increase Metabolic Risk in Adolescents: A 15-Year Follow-Up of a Cluster-Randomized Controlled Trial. J Nutr.2015;145:2749-55. | IV
516 | Santos,I.,Victora,C. G.,Martines,J.,Goncalves,H.,Gigante,D. P.,Valle,N. J.,Pelto,G. Nutrition counseling increases weight gain among Brazilian children. J Nutr.2001;131:2866-73. | IV
517 | Satter, Ma,Jabin, Sa,Abedin, N.,Mf, Mf,Parvin, R.,Dhali, M.,Amin, Mz. Development and Evaluation of Weaning Foods Using Locally Available Nutritious Fruits in Bangladesh. Malaysian Journal of Nutrition.2014;20:83-92. | Design, IV, DV
518 | Savino, F.,Maccario, S.,Cresi, F.,Grasso, G.,Oggero, R.,Silvestro, L.,Mussa, G. C. Bioimpedance vector analysis in breastfed and formula-fed infants in the first six months of life. Adv Exp Med Biol.2004;554:501-4. | Design, IV
519 | Savino, F.,Sorrenti, M.,Benetti, S.,Lupica, M. M.,Liguori, S. A.,Oggero, R. Resistin and leptin in breast milk and infants in early life. Early Hum Dev.2012;88:779-82. | Design, IV
520 | Sawley, L. Infant feeding. Nursing (Lond).1989;3:18-23. | Design
521 | Sazawal,S.,Dhingra,P.,Dhingra,U.,Gupta,S.,Iyengar,V.,Menon,V. P.,Sarkar,A.,Black,R. E. Compliance with home-based fortification strategies for delivery of iron and zinc: its effect on haematological and growth markers among 6-24 months old children in north India. J Health Popul Nutr.2014;32:217-26. | Country
522 | Scaglioni, S.,Agostoni, C.,Notaris, R. D.,Radaelli, G.,Radice, N.,Valenti, M.,Giovannini, M.,Riva, E. Early macronutrient intake and overweight at five years of age. Int J Obes Relat Metab Disord.2000;24:777-81. | IV
523 | Scheiwe, A.,Hardy, R.,Watt, R. G. Four-year follow-up of a randomized controlled trial of a social support intervention on infant feeding practices. Matern Child Nutr.2010;6:328-37. | IV
524 | Schmalz, M.,Boos, K.,Schmalz, G.,Huntington, M. K. Failure to thrive. J Fam Pract.2009;58:539-44. | Design
525 | Schmidt,M. K.,Muslimatun,S.,West,C. E.,Schultink,W.,Gross,R.,Hautvast,J. G. Nutritional status and linear growth of Indonesian infants in west java are determined more by prenatal environment than by postnatal factors. J Nutr.2002;132:2202-7. | Country
526 | Schroeder, D. G.,Martorell, R.,Rivera, J. A.,Ruel, M. T.,Habicht, J. P. Age differences in the impact of nutritional supplementation on growth. J Nutr.1995;125:1051s-1059s. | IV
527 | Schroeder, N.,Rushovich, B.,Bartlett, E.,Sharma, S.,Gittelsohn, J.,Caballero, B. Early Obesity Prevention: A Randomized Trial of a Practice-Based Intervention in 0-24-Month Infants. J Obes.2015;2015:795859. | IV
528 | Schwartz, R.,Vigo, A.,de Oliveira, L. D.,Justo Giugliani, E. R. The Effect of a Pro-Breastfeeding and Healthy Complementary Feeding Intervention Targeting Adolescent Mothers and Grandmothers on Growth and Prevalence of Overweight of Preschool Children. PLoS One.2015;10:e0131884. | IV
529 | Scott, J. A.,Binns, C. W.,Graham, K. I.,Oddy, W. H. Predictors of the early introduction of solid foods in infants: results of a cohort study. BMC Pediatr.2009;9:60. | DV
530 | Scott, J. A.,Dashti, M.,Al-Sughayer, M.,Edwards, C. A. Timing and Determinants of the Introduction of Complementary Foods in Kuwait: Results of a Prospective Cohort Study. J Hum Lact.2015;31:467-73. | DV
531 | Scully, T. Obesity. Nature.2014;508:S49. | Design
532 | Seal, N.,Broome, M. E. Prepregnancy Body Mass Index and Feeding Practices in Relation to Infants’ Growth. J Nurse Pract.2013;9. | Design
533 | Seksaria,S. A.,Sheth,M. K. Mass media as a means to bring about behavioral changes in infant and young child feeding practices amongst tribal mothers of Chikhli taluka, Gujarat. Indian Journal of Public Health Research and Development.2015;6:113-118. | Design, IV
534 | Sellen, D. W.,Thompson, A. L.,Hruschka, D. J.,Stein, A. D.,Martorell, R. Early determinants of non-exclusive breastfeeding among Guatemalan infants. Adv Exp Med Biol.2004;554:299-301. | IV, DV
535 | Senarath, U.,Godakandage, S. S.,Jayawickrama, H.,Siriwardena, I.,Dibley, M. J. Determinants of inappropriate complementary feeding practices in young children in Sri Lanka: secondary data analysis of Demographic and Health Survey 2006-2007. Matern Child Nutr.2012;8 Suppl 1:60-77. | Design,DV
536 | Sethi, V.,Kashyap, S.,Seth, V. Effect of nutrition education of mothers on infant feeding practices. Indian J Pediatr.2003;70:463-6. | IV
537 | Sezer,R. G.,Aydemir,G.,Akcan,A. B.,Bayoglu,D. S.,Guran,T.,Bozaykut,A. Effect of breastfeeding on serum zinc levels and growth in healthy infants. Breastfeed Med.2013;8:159-63. | Design
538 | Shaternikov,V. A.,Fateeva,E. M.,Chernikov,M. N. Protein nutrition in early infancy and subsequent periods: its effect on further development. Bibl Nutr Dieta.1982:95-111. | Design
539 | Shehadeh, N.,Weitzer-Kish, H.,Shamir, R.,Shihab, S.,Weiss, R. Impact of early postnatal weight gain and feeding patterns on body mass index in adolescence. J Pediatr Endocrinol Metab.2008;21:9-15. | IV
540 | Shi,L.,Zhang,J.,Wang,Y.,Caulfield,L. E.,Guyer,B. Effectiveness of an educational intervention on complementary feeding practices and growth in rural China: a cluster randomised controlled trial. Public Health Nutr.2010;13:556-65. | IV
541 | Shim, J. E.,Kim, J.,Mathai, R. A. Associations of infant feeding practices and picky eating behaviors of preschool children. J Am Diet Assoc.2011;111:1363-8. | DV
542 | Simell, O.,Niinikoski, H.,Viikari, J.,Rask-Nissila, L.,Tammi, A.,Ronnemaa, T. Cardiovascular disease risk factors in young children in the STRIP baby project. Special Turku coronary Risk factor Intervention Project for children. Ann Med.1999;31 Suppl 1:55-61. | IV
543 | Simondon, K. B.,Gartner, A.,Berger, J.,Cornu, A.,Massamba, J. P.,San Miguel, J. L.,Ly, C.,Missotte, I.,Simondon, F.,Traissac, P.,Delpeuch, F.,Maire, B. Effect of early, short-term supplementation on weight and linear growth of 4-7-mo-old infants in developing countries: a four-country randomized trial. Am J Clin Nutr.1996;64:537-45. | IV,Country
544 | Singhal A,Cole TJ,Fewtrell M,Kennedy K,Stephenson T,Elias-Jones A,Lucas A. Promotion of faster weight gain in infants born small for gestational age: is there an adverse effect on later blood pressure?. Circulation.2007;115:213-20. | Health status, IV
545 | Singhal, A.,Lucas, A. Early origins of cardiovascular disease: is there a unifying hypothesis?. Lancet.2004;363:1642-5. | Design
546 | Skau,J. K.,Touch,B.,Chhoun,C.,Chea,M.,Unni,U. S.,Makurat,J.,Filteau,S.,Wieringa,F. T.,Dijkhuizen,M. A.,Ritz,C.,Wells,J. C.,Berger,J.,Friis,H.,Michaelsen,K. F.,Roos,N. Effects of animal source food and micronutrient fortification in complementary food products on body composition, iron status, and linear growth: a randomized trial in Cambodia. Am J Clin Nutr.2015;101:742-51. | IV
547 | Skledar, M. T.,Milosevic, M. Breastfeeding and time of complementary food introduction as predictors of obesity in children. Cent Eur J Public Health.2015;23:26-31. | Design
548 | Sloan, S.,Gildea, A.,Stewart, M.,Sneddon, H.,Iwaniec, D. Early weaning is related to weight and rate of weight gain in infancy. Child Care Health Dev.2008;34:59-64. | Design
549 | Snijders, B. E.,Thijs, C.,van Ree, R.,van den Brandt, P. A. Age at first introduction of cow milk products and other food products in relation to infant atopic manifestations in the first 2 years of life: the KOALA Birth Cohort Study. Pediatrics.2008;122:e115-22. | DV
550 | Soto-Ramirez, N.,Karmaus, W.,Zhang, H.,Davis, S.,Agarwal, S.,Albergottie, A. Modes of infant feeding and the occurrence of coughing/wheezing in the first year of life. J Hum Lact.2013;29:71-80. | IV, DV
551 | Sparks, J. W. Fetal growth and diet. Mead Johnson Symp Perinat Dev Med.1984:21-7. | Design
552 | Specker BL,Beck A,Kalkwarf H,Ho M. Randomized trial of varying mineral intake on total body bone mineral accretion during the first year of life. Pediatrics.1997;99:E12. | IV
553 | Spence,A. C.,Campbell,K. J.,Crawford,D. A.,McNaughton,S. A.,Hesketh,K. D. Mediators of improved child diet quality following a health promotion intervention: the Melbourne InFANT Program. Int J Behav Nutr Phys Act.2014;11:137. | IV, DV
554 | Sreedhara, M. S.,Banapurmath, C. R. A study of nutritional status of infants in relation to their complementary feeding practices. Current Pediatric Research.2014;18:39-41. | Design
555 | Stahl, M. D.,Guida, D. A. Slow weight gain in the breast-fed infant: management options. Pediatr Nurs.1984;10:117-20, 164. | Design
556 | Stang,J. Improving the eating patterns of infants and toddlers. J Am Diet Assoc.2006;106:S7-9. | Design
557 | Stifter, C. A.,Anzman-Frasca, S.,Birch, L. L.,Voegtline, K. Parent use of food to soothe infant/toddler distress and child weight status. An exploratory study. Appetite.2011;57:693-9. | Design, IV
558 | Strbak, V.,Skultetyova, M.,Hromadova, M.,Randuskova, A.,Macho, L. Late effects of breast-feeding and early weaning: seven-year prospective study in children. Endocr Regul.1991;25:53-7. | IV
559 | Stuff, J. E.,Garza, C.,Boutte, C.,Fraley, J. K.,Smith, E. O.,Klein, E. R.,Nichols, B. L. Sources of variance in milk and caloric intakes in breast-fed infants: implications for lactation study design and interpretation. Am J Clin Nutr.1986;43:361-6. | Design, IV
560 | Stuff, J. E.,Nichols, B. L. Nutrient intake and growth performance of older infants fed human milk. J Pediatr.1989;115:959-68. | DV
561 | Stunkard, A. J.,Berkowitz, R. I.,Schoeller, D.,Maislin, G.,Stallings, V. A. Predictors of body size in the first 2 y of life: a high-risk study of human obesity. Int J Obes Relat Metab Disord.2004;28:503-13. | IV
562 | Stunkard, A. J.,Berkowitz, R. I.,Stallings, V. A.,Schoeller, D. A. Energy intake, not energy output, is a determinant of body size in infants. Am J Clin Nutr.1999;69:524-30. | IV
563 | Super, C. M.,Herrera, M. G.,Mora, J. O. Long-term effects of food supplementation and psychosocial intervention on the physical growth of Colombian infants at risk of malnutrition. Child Dev.1990;61:29-49. | IV
564 | Svahn,J. C.,Feldl,F.,Raiha,N. C.,Koletzko,B.,Axelsson,I. E. Different quantities and quality of fat in milk products given to young children: effects on long chain polyunsaturated fatty acids and trans fatty acids in plasma. Acta Paediatr.2002;91:20-9. | DV
565 | Taitz, L. S.,Lukmanji, Z. Alterations in feeding patterns and rates of weight gain in South Yorkshire infants, 1971-1977. Hum Biol.1981;53:313-20. | IV, Date
566 | Taitz, L. Feeding children in the first year of life. Midwife Health Visitor & Community Nurse.1990;26:81-84. | Design
567 | Tann, S. P.,Wheeler, E. F. Food intakes and growth of young Chinese children in London. Community Med.1980;2:20-4. | IV, DV
568 | Tantracheewathorn,S.,Lohajaroensub,S. Incidence and risk factors of iron deficiency anemia in term infants. J Med Assoc Thai.2005;88:45-51. | IV, DV
569 | Tanzer F,Gumuser C. A study of the growth of 200 newborn babies for a period of 6 months according to the type of nutrition. Ann Trop Paediatr.1989;9:54-8. | IV
570 | Tarrant, M.,Fong, D. Y.,Wu, K. M.,Lee, I. L.,Wong, E. M.,Sham, A.,Lam, C.,Dodgson, J. E. Breastfeeding and weaning practices among Hong Kong mothers: a prospective study. BMC Pregnancy Childbirth.2010;10:27. | DV
571 | Taveras EM,Blackburn K,Gillman MW,Haines J,McDonald J,Price S,Oken E. First steps for mommy and me: a pilot intervention to improve nutrition and physical activity behaviors of postpartum mothers and their infants. Matern Child Health J.2011;15:1217-27. | IV
572 | Tawia, S. Breastfeeding, brain structure and function, cognitive development and educational attainment. Breastfeed Rev.2013;21:15-20. | Design
573 | Tawia, S. Childhood obesity and being breastfed. Breastfeed Rev.2013;21:42-8. | Design
574 | Taylor,A.,Redworth,E. W.,Morgan,J. B. Influence of diet on iron, copper, and zinc status in children under 24 months of age. Biol Trace Elem Res.2004;97:197-214. | DV
575 | Thakur, R.,Singh, M. G.,Chaudhary, S.,Manuja, N. Effect of mode of delivery and feeding practices on acquisition of oral Streptococcus mutans in infants. Int J Paediatr Dent.2012;22:197-202. | DV
576 | Theron, M.,Amissah, A.,Kleynhans, I. C.,Albertse, E.,MacIntyre, U. E. Inadequate dietary intake is not the cause of stunting amongst young children living in an informal settlement in Gauteng and rural Limpopo Province in South Africa: the NutriGro study. Public Health Nutr.2007;10:379-89. | Design
577 | Thomson, J. L.,Tussing-Humphreys, L. M.,Goodman, M. H. Delta Healthy Sprouts: a randomized comparative effectiveness trial to promote maternal weight control and reduce childhood obesity in the Mississippi Delta. Contemp Clin Trials.2014;38:82-91. | Design, IV
578 | Thorisdottir, B.,Gunnarsdottir, I.,Thorisdottir, A. V.,Palsson, G. I.,Halldorsson, T. I.,Thorsdottir, I. Nutrient intake in infancy and body mass index at six years in two population-based cohorts recruited before and after revision of infant dietary recommendations. Ann Nutr Metab.2013;63:145-51. | IV
579 | Thorsdottir, I.,Gunnarsdottir, I.,Palsson, G. I. Birth weight, growth and feeding in infancy: relation to serum lipid concentration in 12-month-old infants. Eur J Clin Nutr.2003;57:1479-85. | IV, DV
580 | Timby, N.,Domellof, E.,Hernell, O.,Lonnerdal, B.,Domellof, M. Neurodevelopment, nutrition, and growth until 12 mo of age in infants fed a low-energy, low-protein formula supplemented with bovine milk fat globule membranes: a randomized controlled trial. Am J Clin Nutr.2014;99:860-8. | IV
581 | Townsend, E.,Pitchford, N. J. Baby knows best? The impact of weaning style on food preferences and body mass index in early childhood in a case-controlled sample. BMJ Open.2012;2:e000298. | IV
582 | Tripathy, R.,Das, R. N.,Das, M. M.,Parija, A. C. Growth in the first year in children following IAP Policy on Infant Feeding. Indian Pediatr.2000;37:1051-9. | IV
583 | Tulldahl, J.,Pettersson, K.,Andersson, S. W.,Hulthen, L. Mode of infant feeding and achieved growth in adolescence: early feeding patterns in relation to growth and body composition in adolescence. Obes Res.1999;7:431-7. | Design
584 | Umer, A.,Hamilton, C.,Britton, C. M.,Mullett, M. D.,John, C.,Neal, W.,Lilly, C. L. Association between Breastfeeding and Childhood Obesity: Analysis of a Linked Longitudinal Study of Rural Appalachian Fifth-Grade Children. Child Obes.2015;11:449-55. | IV
585 | Unni, J. C.,Richard, J. Growth and morbidity of breast-fed and artificially-fed infants in urban south Indian families. J Trop Pediatr.1988;34:179-81. | IV
586 | Vail, B.,Prentice, P.,Dunger, D. B.,Hughes, I. A.,Acerini, C. L.,Ong, K. K. Age at Weaning and Infant Growth: Primary Analysis and Systematic Review. Journal of Pediatrics.2015;167:317-324.e1. | Design
587 | Valman, H. B. The first year of life: feeding and feeding problems. Br Med J.1980;280:457-60. | Design
588 | van der Willik, E. M.,Vrijkotte, T. G.,Altenburg, T. M.,Gademan, M. G.,Kist-van Holthe, J. Exclusively breastfed overweight infants are at the same risk of childhood overweight as formula fed overweight infants. Arch Dis Child.2015;100:932-7. | IV
589 | van Dijk, C. E.,Innis, S. M. Growth-curve standards and the assessment of early excess weight gain in infancy. Pediatrics.2009;123:102-8. | IV, DV
590 | van Eijsden, M.,Meijers, C. M.,Jansen, J. E.,de Kroon, M. L.,Vrijkotte, T. G. Cultural variation in early feeding pattern and maternal perceptions of infant growth. Br J Nutr.2015;114:481-8. | DV
591 | van Rheenen,P. F.,de Moor,L. T.,Eschbach,S.,Brabin,B. J. A cohort study of haemoglobin and zinc protoporphyrin levels in term Zambian infants: effects of iron stores at birth, complementary food and placental malaria. Eur J Clin Nutr.2008;62:1379-87. | Country
592 | van t Hof Msc, M. A. The influence of breastfeeding and complementary foods on growth until three years of age in the Euro-Growth Study. Pediatrics.2000;106:1281a-1281. | Design
593 | Vazir,S.,Engle,P.,Balakrishna,N.,Griffiths,P. L.,Johnson,S. L.,Creed-Kanashiro,H.,Fernandez Rao,S.,Shroff,M. R.,Bentley,M. E. Cluster-randomized trial on complementary and responsive feeding education to caregivers found improved dietary intake, growth and development among rural Indian toddlers. Matern Child Nutr.2013;9:99-117. | IV
594 | Veena SR,Krishnaveni GV,Srinivasan K,Wills AK,Hill JC,Kurpad AV,Muthayya S,Karat SC,Nalinakshi M,Fall CH. Infant feeding practice and childhood cognitive performance in South India. Arch Dis Child.2010;95:347-54. | Country
595 | Veena, S. R.,Krishnaveni, G. V.,Wills, A. K.,Hill, J. C.,Karat, S. C.,Fall, C. H. Glucose tolerance and insulin resistance in Indian children: relationship to infant feeding pattern. Diabetologia.2011;54:2533-7. | Country
596 | Vehapoglu, A.,Yazici, M.,Demir, A. D.,Turkmen, S.,Nursoy, M.,Ozkaya, E. Early infant feeding practice and childhood obesity: the relation of breast-feeding and timing of solid food introduction with childhood obesity. J Pediatr Endocrinol Metab.2014;27:1181-7. | Design
597 | Venancio, S. I.,Saldiva, S. R.,Mondini, L.,Levy, R. B.,Escuder, M. M. Early interruption of exclusive breastfeeding and associated factors, state of Sao Paulo, Brazil. J Hum Lact.2008;24:168-74. | Design, DV
598 | Verd S,Barriuso L,Gich I,Gutierrez A,Nadal-Amat J,Carreras E. Risk of early breastfeeding cessation among symmetrical, small for gestational age infants. Ann Hum Biol.2013;40:146-51. | Health status, DV
599 | Victora, C. G.,Matijasevich, A.,Santos, I. S.,Barros, A. J.,Horta, B. L.,Barros, F. C. Breastfeeding and feeding patterns in three birth cohorts in Southern Brazil: trends and differentials. Cad Saude Publica.2008;24 Suppl 3:S409-16. | IV, DV
600 | Victora,C. G.,Vaughan,J. P.,Martines,J. C.,Barcelos,L. B. Is prolonged breast-feeding associated with malnutrition?. Am J Clin Nutr.1984;39:307-14. | IV
601 | Villalpando, S. Feeding mode, infections, and anthropometric status in early childhood. Pediatrics.2000;106:1282-3. | Design
602 | Virtanen, S. M.,Laara, E.,Hypponen, E.,Reijonen, H.,Rasanen, L.,Aro, A.,Knip, M.,Ilonen, J.,Akerblom, H. K. Cow’s milk consumption, HLA-DQB1 genotype, and type 1 diabetes: a nested case-control study of siblings of children with diabetes. Childhood diabetes in Finland study group. Diabetes.2000;49:912-7. | DV
603 | Virtanen, S. M.,Rasanen, L.,Ylonen, K.,Aro, A.,Clayton, D.,Langholz, B.,Pitkaniemi, J.,Savilahti, E.,Lounamaa, R.,Tuomilehto, J.,et al.,. Early introduction of dairy products associated with increased risk of IDDM in Finnish children. The Childhood in Diabetes in Finland Study Group. Diabetes.1993;42:1786-90. | DV
604 | Vobecky,J. S.,Vobecky,J.,Shapcott,D.,Demers,P. P. Nutrient intake patterns and nutritional status with regard to relative weight in early infancy. Am J Clin Nutr.1983;38:730-8. | IV
605 | Wandel, M.,Fagerli, R. Aa,Olsen, P. T.,Borch-Iohnsen, B.,Ek, J. Iron status and weaning practices among Norwegian and immigrant infants. Nutrition Research.1996;16:251-265. | Design
606 | Wang RJ,Trehan I,LaGrone LN,Weisz AJ,Thakwalakwa CM,Maleta KM,Manary MJ. Investigation of food acceptability and feeding practices for lipid nutrient supplements and blended flours used to treat moderate malnutrition. J Nutr Educ Behav.2013;45:258-63. | Health status, Country
607 | Watt, R. G.,Tull, K. I.,Hardy, R.,Wiggins, M.,Kelly, Y.,Molloy, B.,Dowler, E.,Apps, J.,McGlone, P. Effectiveness of a social support intervention on infant feeding practices: randomised controlled trial. J Epidemiol Community Health.2009;63:156-62. | IV, DV
608 | Weber, M.,Grote, V.,Closa-Monasterolo, R.,Escribano, J.,Langhendries, J. P.,Dain, E.,Giovannini, M.,Verduci, E.,Gruszfeld, D.,Socha, P.,Koletzko, B. Lower protein content in infant formula reduces BMI and obesity risk at school age: follow-up of a randomized trial. Am J Clin Nutr.2014;99:1041-51. | IV
609 | Weijs, P. J.,Kool, L. M.,van Baar, N. M.,van der Zee, S. C. High beverage sugar as well as high animal protein intake at infancy may increase overweight risk at 8 years: a prospective longitudinal pilot study. Nutr J.2011;10:95. | IV
610 | Wen, L. M.,Baur, L. A.,Simpson, J. M.,Xu, H.,Hayes, A. J.,Hardy, L. L.,Williams, M.,Rissel, C. Sustainability of Effects of an Early Childhood Obesity Prevention Trial Over Time: A Further 3-Year Follow-up of the Healthy Beginnings Trial. JAMA Pediatr.2015;169:543-51. | IV
611 | West, C. E.,Hernell, O.,Andersson, Y.,Sjostedt, M.,Hammarstrom, M. L. Probiotic effects on T-cell maturation in infants during weaning. Clin Exp Allergy.2012;42:540-9. | IV, DV
612 | Westphal, R.,Phillips, G.,Irwig, L. M. Infant care and feeding in an urban black population. S Afr Med J.1981;60:778-81. | DV, Date
613 | Weyermann, M.,Rothenbacher, D.,Brenner, H. Duration of breastfeeding and risk of overweight in childhood: a prospective birth cohort study from Germany. Int J Obes (Lond).2006;30:1281-7. | IV
614 | Wharf,S. G.,Fox,T. E.,Fairweather-Tait,S. J.,Cook,J. D. Factors affecting iron stores in infants 4-18 months of age. Eur J Clin Nutr.1997;51:504-9. | Design
615 | Whitehead, R. G.,Paul, A. A.,Ahmed, E. A. Weaning practices in the United Kingdom and variations in anthropometric development. Acta Paediatr Scand Suppl.1986;323:14-23. | Design, IV
616 | Whitehead, R. G.,Paul, A. A. Infant growth and human milk requirements. A fresh approach. Lancet.1981;2:161-3. | IV
617 | Whitten, C. F.,Stewart, R. A. The effect of dietary sodium in infancy on blood pressure and related factors. Studies of infants fed salted and unsalted diets for five months at eight months and eight years of age. Acta Paediatr Scand Suppl.1980;279:1-17. | IV
618 | Wiberger, M.,Eiben, G.,Lissner, L.,Mehlig, K.,Papoutsou, S.,Hunsberger, M. Children consuming milk cereal drink are at increased risk for overweight: The IDEFICS Sweden study, on behalf of the IDEFICS Consortium. Scand J Public Health.2014;42:518-24. | Design
619 | Wigg, N. R.,Tong, S.,McMichael, A. J.,Baghurst, P. A.,Vimpani, G.,Roberts, R. Does breastfeeding at six months predict cognitive development?. Aust N Z J Public Health.1998;22:232-6. | IV
620 | Wijga,A.,Vyas,U.,Vyas,A.,Sharma,V.,Pandya,N.,Nabarro,D. Feeding, illness and nutritional status of young children in rural Gujarat. Hum Nutr Clin Nutr.1983;37:255-69. | Design, IV
621 | Williams, D. M.,Martin, R. M.,Davey Smith, G.,Alberti, K. G.,Ben-Shlomo, Y.,McCarthy, A. Associations of infant nutrition with insulin resistance measures in early adulthood: evidence from the Barry-Caerphilly Growth (BCG) study. PLoS One.2012;7:e34161. | IV, DV
622 | Williams, J.,Wolff, A.,Daly, A.,MacDonald, A.,Aukett, A.,Booth, I. W. Iron supplemented formula milk related to reduction in psychomotor decline in infants from inner city areas: randomised study. Bmj.1999;318:693-7. | IV
623 | Winick, M. The role of early nutrition in subsequent development and optimal future health. Bull N Y Acad Med.1989;65:1020-5. | Design
624 | Winkelstein,M. L. Overfeeding in infancy: the early introduction of solid foods. Pediatr Nurs.1984;10:205-8, 236. | Design
625 | Wölfle, J. Growth and puberty in German children: is there still a positive secular trend? In reply..Consumption of milk as a vital factor in growth development. Melnik B, Dtsch Arzetebl 2009, volume 206. Deutsches Aerzteblatt International.2009;106:656-656. | Design
626 | Wright, C. M.,Parkinson, K. N.,Drewett, R. F. Why are babies weaned early? Data from a prospective population based cohort study. Arch Dis Child.2004;89:813-6. | DV
627 | Wright, C. M.,Parkinson, K.,Scott, J. Breast-feeding in a UK urban context: who breast-feeds, for how long and does it matter?. Public Health Nutr.2006;9:686-91. | IV
628 | Wright, M. J.,Bentley, M. E.,Mendez, M. A.,Adair, L. S. The interactive association of dietary diversity scores and breast-feeding status with weight and length in Filipino infants aged 6-24 months. Public Health Nutr.2015;18:1762-73. | Country
629 | Yew, K. S.,Webber, B.,Hodges, J.,Carter, N. J. Clinical inquiries: are there any known health risks to early introduction of solids to an infant’s diet?. J Fam Pract.2009;58:219-20. | Design
630 | Young RJ,Antonson DL,Ferguson PW,Murray ND,Merkel K,Moore TE. Neonatal and infant feeding: effect on bone density at 4 years. J Pediatr Gastroenterol Nutr.2005;41:88-93. | Design
631 | Yousafzai, A. K.,Rasheed, M. A.,Rizvi, A.,Armstrong, R.,Bhutta, Z. A. Effect of integrated responsive stimulation and nutrition interventions in the Lady Health Worker programme in Pakistan on child development, growth, and health outcomes: a cluster-randomised factorial effectiveness trial. Lancet.2014;384:1282-93. | Country
632 | Ystrom, E. Breastfeeding cessation and symptoms of anxiety and depression: a longitudinal cohort study. BMC Pregnancy Childbirth.2012;12:36. | IV, DV
633 | Zadik Z,Borondukov E,Zung A,Reifen R. Adult height and weight of breast-fed and bottle-fed Israeli infants. J Pediatr Gastroenterol Nutr.2003;37:462-7. | IV
634 | Zaman, S.,Jalil, F.,Saleemi, M. A.,Mellander, L.,Ashraf, R. N.,Hanson, L. A. Changes in feeding patterns affect growth in children 0-24 months of age living in socioeconomically different areas of Lahore, Pakistan. Adv Exp Med Biol.2002;503:49-56. | Country
635 | Zaman,S.,Ashraf,R. N.,Martines,J. Training in complementary feeding counselling of healthcare workers and its influence on maternal behaviours and child growth: a cluster-randomized controlled trial in Lahore, Pakistan. J Health Popul Nutr.2008;26:210-22. | IV, Country
636 | Zavaleta,N.,Kvistgaard,A. S.,Graverholt,G.,Respicio,G.,Guija,H.,Valencia,N.,Lonnerdal,B. Efficacy of an MFGM-enriched complementary food in diarrhea, anemia, and micronutrient status in infants. J Pediatr Gastroenterol Nutr.2011;53:561-8. | DV
637 | Zhang,J.,Shi,L.,Chen,D. F.,Wang,J.,Wang,Y. Effectiveness of an educational intervention to improve child feeding practices and growth in rural China: updated results at 18 months of age. Matern Child Nutr.2013;9:118-29. | IV
638 | Zhu, B.,Zhang, J.,Qiu, L.,Binns, C.,Shao, J.,Zhao, Y.,Zhao, Z. Breastfeeding Rates and Growth Charts--the Zhejiang Infant Feeding Trial. Int J Environ Res Public Health.2015;12:7337-47. | IV, DV
639 | Ziegler, E. E.,Fields, D. A.,Chernausek, S. D.,Steenhout, P.,Grathwohl, D.,Jeter, J. M.,Nelson, S. E.,Haschke, F. Adequacy of Infant Formula With Protein Content of 1.6 g/100 kcal for Infants Between 3 and 12 Months. J Pediatr Gastroenterol Nutr.2015;61:596-603. | IV
640 | Ziegler,E. E.,Fomon,S. J.,Nelson,S. E.,Rebouche,C. J.,Edwards,B. B.,Rogers,R. R.,Lehman,L. J. Cow milk feeding in infancy: further observations on blood loss from the gastrointestinal tract. J Pediatr.1990;116:11-8. | IV, DV
641 | Zive, M. M.,McKay, H.,Frank-Spohrer, G. C.,Broyles, S. L.,Nelson, J. A.,Nader, P. R. Infant-feeding practices and adiposity in 4-y-old Anglo- and Mexican-Americans. Am J Clin Nutr.1992;55:1104-8. | Design
642 | Zutavern, A.,Brockow, I.,Schaaf, B.,von Berg, A.,Diez, U.,Borte, M.,Kraemer, U.,Herbarth, O.,Behrendt, H.,Wichmann, H. E.,Heinrich, J. Timing of solid food introduction in relation to eczema, asthma, allergic rhinitis, and food and inhalant sensitization at the age of 6 years: results from the prospective birth cohort study LISA. Pediatrics.2008;121:e44-52. | DV

1 Abbreviations: DV- Dependent variable; IV- Independent variable/exposure/intervention