# APPENDIX

This table describes the characteristics of included studies in alphabetical order of first author’s last name.

Supplemental Table S1 Description of studies examining types and amounts of complementary foods and beverages consumed and growth, size, and body composition

[underlined: Study] | [underlined: Intervention/Exposures] | [underlined: Outcomes] | [underlined: Confounders & Limitations]
Abraham, 2012; Prospective Cohort Study; Scotland; [underlined: Sample Size]:; Baseline N: 5,217; Analytic N: 4,493; Attrition: 13.9%; Power Analysis: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; 4% non-white ethnic group (Bradshaw, 2007); [underlined: Background Diet]:; BF at 45-48mo: 61.0% ever BF, 39.0% never BF; Infants in the negative pattern: 69% ever BF; started CFB at 0-3mo (20%), 4-5mo (64%), and 6-10mo (16%); Infants in the positive pattern: 50% ever BF; started CFB at 0-3mo (12%), 4-5mo (69%), and 6-10mo (20%) | Two dietary patterns were identified at 19-24mo using cluster analysis, and each infant was classified by cluster membership:; Negative pattern: low fruit, vegetable; high sweets, crisps, soft drinks, snacking; Positive pattern: high fruit, vegetable; low snacking; Age:0-24mo; Assessment Methods; Cluster analysis of survey at 19-24mo | Weight status; Age: 45-48mo; Assessment Methods; Weight status: frequency of overweight/obese based on BMIZ >1.04; not overweight/obese ≤ 1.04 (UK 1990 ref. curves); methods used to obtain weight and height NR | SES: X; Birth size: X; [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Key confounders from the analytic framework were NR or adjusted for in analyses including sex, race/ethnicity, maternal age, or birth size/gestational age; Cannot determine if outcome assessors were blinded, primary interviewers were unblinded; Other: IV/Exposure was self-report; Bradshaw, 2007 summarizes Sweep 1 baseline characteristics
Almquist-Tangen, 2013; Prospective Cohort Study; Sweden; [underlined: Sample Size]:; Baseline N: 2,666; Analytic N at 12mo: 2,404; Analytic N at 18mo: 2,241; Attrition at 12mo: 9.8%; Attrition at 18mo: 15.9%; Power Analysis: NR; [underlined: Sex:]; 49.4% female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; At 4mo: 78.7% BF, 74.4% EBF; 21.3% FF; 4.3% MF (BF and FF); At 6 mo, 58.3% BF; 1.6% EBF | Milk cereal drink (MCD) vs. porridge vs. semi-solids MCD (68kcal/100mL) defined as a soup-like liquid offered in a bottle containing: 1.8 g protein, 8.7 g CHO and 2.9 g fat, fortified with calcium, Fe, Zn, iodine and vitamins A, D, E, C, thiamine, niacin, B6 folic acid, B12 and pantothenic acid; Porridge and semi-solids not defined; Age:18mo; Assessment Methods; Y/N consumption of CFB at 6mo | [underlined: Outcomes:]; Weight status; Age: 12mo, 18mo; Assessment Methods; Weight status: “high BMI” defined as 1SD above study population; BMI calculated from measured weight (digital scale) and height (stadiometer) | [underlined: Confounders accounted for:]; Education: X; SES:; Sex: X; Maternal age:; Race/ethnicity:; Feeding practices:; Birth size: X; Gestational age: X; Other: maternal obesity; paternal obesity; paternal education; maternal smoking; BMI at 1, 4, and 6 mo.; [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine reliability/validity of survey items; Did not adjust for potential key confounders (SES, race/ethnicity, feeding practices)
Ay, 2008; Prospective Cohort Study; The Netherlands; [underlined: Sample Size]:; Baseline N: 1232; Analytic N: 1012; Attrition: 17.9%; Power Analysis/Sample Size Calculation: NR; [underlined: Sex:]; 48.2% Female; [underlined: Race/Ethnicity]:; 100% “Dutch ethnicity”; [underlined: Background Diet]:; ~90% ever BF, duration of BF = ~5mo | Age of CFB introduction: <5mo or >5mo; CFB: Fruit snack; Age: 2, 6, and 12mo; Assessment Methods:; Caregiver questionnaire | [underlined: Outcomes:]; Body composition (Adiposity); Age: 24mo; Assessment Methods:; Body composition: sum of skinfold thickness (biceps, triceps, suprailiacal, subscapular) measured by study personnel using calipers | [underlined: Confounders accounted for:]; Education: X; Sex: X; Maternal age: X; Gestational age: X; Other: Smoking; [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Did not adjust for any key confounders (SES, race/ethnicity/feeding practices, birth size)
Baird, 2008; Prospective Cohort Study; United Kingdom; [underlined: Sample Size]:; Baseline N = 1,973; Analytic N = 1,740; Attrition = 11.8%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 46.9% female; [underlined: Race/Ethnicity]:; 94% white; [underlined: Background Diet]:; 0-6mo: 7.5% BF; ~21% FF, ~71.5% MF combination of BF and FF assessed via caregiver-report at 6mo | Two dietary patterns were identified at 6mo using principal component analysis, and each infant received a score for adherence to the pattern:; Infant Guidelines: high frequency of consumption of vegetables, fruit, meat, fish, home-prepared foods, breast milk; low frequency of consumption of commercial baby foods in jars and formula; Adult Foods: high frequency of consumption of bread, savory snacks, biscuits, squash, breakfast cereals, and crisps; low frequency of breast milk, baby rice, and cooked and canned fruit; Age:12mo; Assessment Methods; Timing: Maternal report; Type: FFQ over 7d at 6mo; FFQ over 28d at 12mo; Dietary patterns identified by PCA | [underlined: Outcomes:]; Body composition; Weight; Length; Age: Birth, 6mo, 12mo, 0-6mo; 6-12mo; Assessment Methods; Body composition: triceps and subscapular skinfold calipers; crude and thickness SD score from 0-6mo and 6-12mo; Weight: digital scale; crude and change in weight SD score from 0-6mo and 6-12mo; Length: infantometer; crude and change in length SD score from 0-6mo and 6-12mo | [underlined: Confounders accounted for:]; Education: X; Sex: X; Other: Parity; Smoking; [underlined: Limitations:]; Cannot determine whether groups were similar at baseline; Unclear whether outcome assessors were blinded to the infants’ feeding histories; Did not adjust for potential key confounders (SES, maternal age, race/ethnicity, feeding practices, birth size, gestational age); BF duration and infant diet was retrospectively self-reported by mothers at 6 and 12mo, thus may have been biased; ethnic minorities were underrepresented in this sample.
Barton, 2002; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N = 52; Analytic N = 52; Attrition = 0%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 46% BF, 54% FF at birth; 33% BF, 67% FF at 1-2mo; 83% received CFB <4mo | Two dietary patterns were observed in infants based on intake before or at 4-6mo:; Inappropriate foods: home-prepared mashed potatoes and gravy, green beans with fat-back, pork, bacon, steak, high-sugar high-fat puddings, desserts, soda, and juice >8oz/d; Appropriate foods: Parent-prepared solids w/o extra fat, salt, sugar; Age:4-6mo; Assessment Methods; Caregiver report | [underlined: Outcomes:]; Weight, length, HC; Age: 1-2mo; 4-6mo; Assessment Methods; Weight: measured by study personnel on balance-beam scale; Length: measured by trained personnel, on standard length board; HC: measured by study personnel with nonfabric measuring tape | [underlined: Confounders accounted for:]; Other: NR; [underlined: Limitations:]; Cannot determine whether groups differed at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Length of follow-up varied from 4 to 6mo of age; Cannot determined validity/reliability of measures used to assess outcomes; Did not adjust for any potential key confounders (including education, SES, sex, maternal age, race/ethnicity, feeding practices, birth size, gestational age) Did not adjust for baseline values though weight/length at 1-2mo was similar between groups; Groups were unbalanced (40 infants in the CFB <4mo group vs. 8 infants in the >4mo group)
Bell, 2013; Prospective Cohort Study; Australia; [underlined: Sample Size]:; Baseline N = 552; Analytic N = 493; Attrition = 10.7%; Power Analysis: NR; [underlined: Sex:]; 54% female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 3% never BF, 34% BF>6 mo, 29% BF 6-12 mo, 29% BF>12 mo, 6% missing; Age of introduction to solids: 20.9 wk (SD=5.1) | Four dietary patterns were identified at 13-16mo using principal component analysis, and each infant received a score for adherence to the pattern:; Core: fruit, grains, nonwhite bread, vegetables, cheese, eggs, nuts and seeds; Basic combination: basic core + non-core w/o fruit or vegetables; Basic core: white bread, milk; Non-core: spreads, juice, ice-cream; Age:13-16mo; Assessment Methods; 3d multiple-pass 24hr recalls (2d week, 1d weekend); Dietary patterns identified by PCA | [underlined: Outcomes:]; BMIZ; Age: 24mo; Assessment Methods; Body composition: age and sex-specific BMIZ calculated from measured weight/height (measured by trained personnel, physicians, nurses without shoes or garments) | [underlined: Confounders accounted for:]; Education: X; SES: X (SEIFA decile); Sex: X; Maternal age: X; Feeding practices: X; Other: smoking status, marital status, weight status, parity, child age, age of introduction to solids; [underlined: Limitations:]; Cannot determine whether groups differed at baseline on key characteristics; Cannot detrmined wheter outcome assessors were blinded; Cannot determine reliability of outcome assessment, 17% of outcomes measured by general practitioners or child health nurses, not study staff; Did not adjust for birth size, gestational age, or race/ethnicity; Mothers may have reported more favorable dietary intakes (highly educated sample who may have greater knowledge of dietary recommendations)
Cantoral, 2016; Prospective Cohort Study; Mexico; [underlined: Sample Size]:; Baseline N: 622 (enrolled in F/U); Analytic N: 227; Attrition: ~64%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 54% female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 31% at least partial BF; 73% introduced to SSB <12mo | Age of CFB introduction: ≤12mo vs >12mo; CFB: SSB: sum of daily intake of soda, commercial fruit drinks, flavored water with sugar; Not including natural fruit or vegetable juice; Age: 12mo; every 6mo until 5y; at 8-14y; Assessment Methods:; 116-item FFQ | Weight status; WC; Age: 8-14y; Assessment Methods:; Weight status: risk of obesity classified as BMI>2 SD of z-score; BMI from measured weight (digital scale to 0.1kg) and height (stadiometer to 0.1cm); WC: measuring tape to 0.1cm for abdominal obesity: WC≥ 90th %tile | [underlined: Confounders accounted for:]; SES: X; Sex: X; Feeding practices: X; Other: non-SSB intake, TV watching, physical activity, maternal obesity at 12mo post-partum; [underlined: Limitations:]; Cannot determine whether groups differed at baseline on key characteristics; Cannot determine if outcome assessors were blinded; Did not account for high attrition rate; Did not adjust for key confounders of education, maternal age, race/ethnicity, birth size or gestational age; Risk for measurement error associated with FFQ; Assumes that SSB intake was constant during the months evaluated on FFQ
Carruth, 2000; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N = 98; Analytic N = 94; Attrition = 4.1%; Power Analysis and Sufficient Sample Size: Use of an incomplete block design maintained statistical power; [underlined: Sex:]; 48.0% female (Skinner, 1997); [underlined: Race/Ethnicity]:; 100% White; [underlined: Background Diet]:; 83% any BF, 33% EBF at 4mo, 33% MF at 4mo; 12% EBF at 6mo; ~64% CFB by 4mo; Median age for introducing CFB: cereal 4.0 (range .50–6.5 mo), juice 4.50 (1–11 mo), fruit 5.0 (.50–8.2 mo), vegetables 5.5 (1–7.7 mo) and the food cluster (mixed foods, table foods, meat) 7.0 (3–12 mo) | Food cluster: yes/no if any meats, mixed foods or table foods; Vegetables: yes/no; CFB: 1 or more foods including cereal, juice, fruits, vegetables, meat, mixed food, and table foods; Infant could still be BF or FF with CFB; Mean age of introduction of cereal = 4.0mo, juice = 4.5mo, fruit = 5.0mo, vegetables = 5.5mo, food cluster (mixed foods, table foods, meat) = 7.0mo; Age: 2, 3, 4, 6, 8, 10, 12, 16, 20, and 24mo; Assessment Methods; 24h recall | Weight change; Age: 2-8mo; Assessment Methods; Weight slope: kg/mo; standard protocol; Length slope: cm/mo; standard protocol; Interview schedules were done using an incomplete block design, such that the number of times measures were taken for each infant 3-5 times from 2 to 10mo, and 2-4 times from 12 to 24mo | [underlined: Confounders accounted for:]; Sex: X; Other: Final model 2-8mo rate of change weight: gender, length slope; [underlined: Limitations:]; Cannot determine whether groups differed at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine adequacy of statistical methods (prior versions of regression models not described, data not shown); Did not adjust for potential key confounders (education, SES, maternal age, race/ethnicity, birth size, or gestational age); Limited generalizability (small sample of white middle- to upper class subjects from TN); Results reports only age of intro of vegetables and food cluster remained as significant predictors in rate of change in weight but age of any foods not significant predictor in weight gain 12-24mo; Unclear how addition of cereal ≤4 or >4mo was analyzed in relation to weight outcomes
Dagnelie, 1994; Prospective Cohort Study; The Netherlands; [underlined: Sample Size]:; Baseline N: 110; Analytic N: 106; Attrition: 3.6%; Power Analysis/Sample Size Calculation: NR; [underlined: Sex:]; ~49.0% Female; [underlined: Race/Ethnicity]:; 100% White; [underlined: Background Diet]:; Macrobiotic: BF for ~13mo; Omnivorous: BF for ~6.5mo | Two dietary patterns were observed in infants based on diet followed at weaning,~4-10mo:; Macrobiotic diet: Included unpolished rice, pulses and vegetables with a high fiber content, small additions of seaweeds, fermented foods, nuts, seeds, and seasoned foods; Avoided vitamin D supplements, products of animal origin such as meat and dairy product, fat/oil, and fish.; Omnivorous diet: Not described; Age:4mo-18mo, each cohort followed for 6mo Assessment Methods; Food record, 3d, weighed | Weight status; Body composition; Weight; Length; Circumferences; Age: 4-18mo; Assessment Methods; Results in Dagnelie, 1989 reported as velocities (units/year); Weight, length, sitting height: measured without clothing on Seca scale; flexible steel tape; used to obtain weight-for-length; Crown-heel length, crown-rump length: supine infantometer (for infants <2y); HC, MUAC, biiliacal (pelvic) width: plastic insertion tape; used to obtain fat and muscle areas of arm; Skinfold thickness: Triceps and subscapular via caliper to 0.2mm; Wasting: arm-muscle-area calculated from MUAC and tricep skinfold | [underlined: Confounders accounted for:]; Education: X; Sex: X; Other: Birthweight self-reported; unclear if adjusted for rickets; [underlined: Limitations:]; Strategy to recruit/allocate participants was not similar across groups; Groups differed at baseline on birth weight and feeding practices and cannot determine if these were adjusted for in analyses; Cannot determine the level of adherence to macrobiotic diet, or omnivorous control diet, as specific details regarding diet not provided; Did not adjust for potential key confounders (SES, maternal age, race/ethnicity, feeding practices, birth size, gestational age; Cannot determine when outcomes were assessed; Growth deficit in macrobiotic infants driven by the 8-14mo cohort, with significantly lower triceps skinfold, arm fat area, and lower growth rate, relative to omnivorous infants.; Combination of lack of energy and protein may have caused gowth retardation in weight and MUAC; Cannot determine if rickets and vitamin D deficiency were adjusted for as macrobiotic vs. omnivorous infants had greater rates of both
Davidsson, 1996; Cross-Over Study; Scotland; [underlined: Sample Size]:; Baseline N: 57; Analytic N: 57; Attrition: 0%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; ~53% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 100% FF (CM, no soy) | Cereal varied by fiber content for 4wk:; Wheat/soy: 8% fiber (A) or 1.8% fiber (B); Wheat/milk: 5.3% fiber (C) or 2% fiber (D); Cereal ad lib (~10-60g servings); Additional weaning foods were provided upon request (apple puree, apple juice, exotic fruit juice, and maize puree);; Age: 7-17wk; Assessment Methods; Cereal intake was quantified by weighing the containers before the start of the study and at each visit to the homes every 14d | Weight; Length; Circumferences; Age: 7-17wk; Assessment Methods Weight, height, arm and chest circumference in cm, and HC in cm were measured monthly | [underlined: Confounders accounted for:]; Other: NR; [underlined: Limitations:]; Cannot determine whether groups differed at baseline on key characteristics; Cannot determine if outcome assessors or investigators were blinded; Cannot determine influence from intake of other weaning foods provided; Adherence not described; Cannot determine relability/validity of outcome assessment; Cross-over design but characteristics not described
de Silva, 2007; Non-Randomized Controlled Trial; Sri Lanka; [underlined: Sample Size]:; Baseline N: 182; Analytic N: 152; Attrition: 16.5%; Power: NR; [underlined: Sex:]; ~62% female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; ~22.9% receiving formula; ~75% EBF for 4mo | Intervention: home-based CFB (containing 110-130 kcal/100 ml) + recipes + mechanical blender from 4-12mo; Control: CFB of mothers’ choice from 4-12mo; Age: 8mo; Assessment Methods; Maternal questionnaire and interview | Weight; Length; Age: 4-12mo; Assessment Methods; Weight: gain; measuerd via digital scale monthly; Length: gain, measured via standard infantometer monthly | [underlined: Confounders accounted for:]; Education: X; SES: X; Maternal age: X; Birth size: X; [underlined: Limitations:]; Group allocation methods were not described; Cannot determine whether groups differed at baseline on key characteristics; Cannot determine if investigators and outcome assessors were blinded; Statistical methods were not described; Cannot determine validity/reliabiilty of outcome assessment; Did not adjust for potential key confounders (sex, race/ethnicity, feeding practices though # of feeds identical, or gestational age); Influence of having the recipes and blender available could be concurrent IV/Exposure aside from CFB itself; Race/ethnicity data was lacking; information on maternal health was lacking; data on z scores for weight for age not adequately presented
Dube, 2010; Randomized Controlled Trial; Germany; [underlined: Sample Size]:; Baseline N: 132; Analytic N : 97; Attrition: 26.6%; Sample Size Calculation: N=74 to detect a 1SD difference in Hb; [underlined: Sex:]; 49.5% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; Fully BF at 17wk: ~55%; Fully BF at 26wk: ~16%; Partially BF at 10mo: 23%; Start of CF: ~22wk | High Meat Group (HM): Received commercial baby jars from 4-11mo with meat content of 12% by weight (according to pediatric guidelines); 20g/d 4-7mo, 28.6g/d 8-10mo; Low Meat Group (LM): Received meals 4-11mo with meat content 8% by weight (the lowest level of EU law); ~15g/d 4-7mo; 17.6g/d 8-10mo; 50% of jars contained beef, 50% contained poultry; Parents were advised to start CF by using the study food between 4-6mo, and to continue until 10m, with a frequency of 1 jar/d at least 5 times/wk; Age: 6mo; Assessment Methods; Diet record | Weight; Age: 4, 7, and 10mo; Assessment Methods; Weight and length were measured at the local clinic | [underlined: Confounders accounted for:]; Sex: X; Feeding practices: X; Birth size: All >2.5kg; Gestational age: All full-term; [underlined: Limitations:]; Did not assess the impact of high loss to follow-up (~27%); Cannot determine validity of outcome measurement (weight NR); The small difference between LM (8%) vs. HM (12%) was acknowledged as a limitation; Length was measured but not reported in results
Durmus, 2012; Prospective Cohort Study; The Netherlands; [underlined: Sample Size]:; Baseline N: 1106; Analytic N: 779; Attrition: 29.6%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 49% female; [underlined: Race/Ethnicity]:; 100% “Dutch ethnicity”; [underlined: Background Diet]:; 87.5% ever BF; ~4.5mo BF duration | Fruit and/or vegetable snack first given (<4, 4-5, >5mo); Age: 2, 6, and 12mo; Assessment Methods:; Caregiver questionnaire | Body composition (Adiposity); Age: 6mo, 24mo; Assessment Methods:; Body composition:; - Subcutaneous fat mass via skinfold thickness (biceps, triceps, suprailiacal, subscapular) measured by study personnel using calipers | [underlined: Confounders accounted for:]; Education: X; Sex: X; Feeding practices: X; Birth size: X (Birth weight); Gestational age: X; Other: Maternal BMI, Smoking; Parity; Current height; Observer; [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on all key characteristics; Cannot determine whether outcome assessors were blinded; Did not assess the impact of high loss to follow-up (~27%); Did not adjust for key confounders (SES, maternal age, race/ethnicity); BF information only available in 78% of sample; CFB included only a fruit or vegetable snack and other products could have been introduced; Homogenous, highly-educated sample;; Limited generalizability
Durmus, 2014; Prospective Cohort Study; The Netherlands; [underlined: Sample Size]:; Baseline N: 6054; Analytic N: 5063; Attrition: 16.4%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 50.2% female; [underlined: Race/Ethnicity]:; 100% “Dutch ethnicity”; [underlined: Background Diet]:; 92.4% ever BF; 20.4% EBF to 4mo | Fruit and/or vegetable snack first given (<4, 4-4.9, ≥5mo); Age: 2, 6, and 12mo; Assessment Methods:; Caregiver questionnaire | [underlined: Outcomes:]; Weight status; Body composition; WC; Age: 6y; Assessment Methods:; Weight status: risk of overweight or obesity based on IOTF categories for BMI; Body composition:; - Adiposity: total fat mass, android-gynoid ratio (DXA); - BMI: calculated from measured height/weight (stadiometer/ mechanical scale); Abdominal/WC: abdomial fat via ultra-sound | [underlined: Confounders accounted for:]; Education: X; Sex: X; Maternal age: X; Race/ethnicity: X; Birth size: X; Gestational age: X; Other: Child age, Child height; Parity; Maternal BMI, Smoking; TV watching; [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on all key characteristics; Cannot determine whether outcome assessors were blinded; Did not adjust for key confounders (SES or feeding practices); Did not collect information on BM consumption or composition
Engelmann, 1998; Randomized Controlled Trial; Denmark; [underlined: Sample Size]:; Baseline N: 55; Analytic N: 41; Attrition: 25.5%; Power Analysis/Sample Size Calculation: NR; Sex:; 29.3% Female; [underlined: Race/Ethnicity]:; NR; Background Diet:; 100% BF (for ≥1/d); HM consumed more formula (p=0.06) than LM; LM consumed more Fe-fortified gruel than HM (p=0.03). Fish, cow’s milk, fruits, vegetables, and other foods (NS); 4600) | Low-meat group (LM): Received a diet with 10g/d of meat; High-meat group (HM): Received a diet with 27g/d of meat; Parents choose from 7 purees containing vegetables and meat (beef, pork, lamb, turkey, cod) prepared in low- and high-meat versions. All other foods were served ad libitum.; Age: 8-10mo; Assessment Methods; Food record, weighed 1/wk | [underlined: Outcomes:]; Body composition; Weight; Length; MUAC; Age: 10mo; Assessment Methods; Body composition: triceps skinfold via calipers; Weight: Electronic scale to 1g; Length (crown-heel): Electronic measuring board to 0.1cm; MUAC: non-stretchable tape; | [underlined: Confounders accounted for:]; Other: all full-term, >2.5kg; Baseline growth measures NSD between groups; birth weight and length significantly higher in LMG; [underlined: Limitations:]; Cannot determine whether group allocation was concealed; Groups differed at baseline (varied in consumption of formula and gruel) and differences were not adjusted for in analyses; Cannot determine whether subjects or investigators were blinded; Cannot determine validity and reliability of outcome assessment; Did not assess the impact of high loss to follow-up (~26%); Did not adjust analyses for potential key confounders (education, SES, sex, feeding practices, race/ethnicity, birth weight, or gestational age); Groups differed on birth weight and length at baseline, and consumption of formula and gruel, and these differences were not controlled for in the analyses
Gaffney, 2012; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N = 4902; Analytic N = 691; Attrition = 85.9%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 49.3% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF intensity in late infancy: 52.1% low, 24.3% medium, 23.6% high | Juice intake intensity according to servings per 2d:; 0 juice/2d, 1 juice/2d, >1 juice/2d; Age:1, 2, 3, 4, 5, 6, 7, 9, 10, and 12mo; Assessment Methods; Maternal questionnaire | WAZ; Age: 12mo; Assessment Methods; WAZ: maternal-report from recent doctor visit; calculated age and sex-specific z scores by CDC standards | [underlined: Confounders accounted for:]; Education: X; SES: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X; Other: Mother’s smoking status, weight gain in pregnancy, pregravid BMI; [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine reliability/validity of outcome assessment and outcome assessors were not blinded due to both feeding and outcome data self-reported by mothers; Did not assess the impact of high loss to follow-up (~40%); Did not adjust analyses for potential confounders (sex, gestational age); Generalizability limited due to sample not being representative (Data not derived from a nationally representative sample, underrepresented minority groups; sample biased toward mothers with more education and higher SES)
Garden, 2011; Prospective Cohort Study; Australia; [underlined: Sample Size]:; Baseline N: 616; Analytic N: 362 (339 WC); Attrition: 41.2% (44.5%); Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; N:362 for BM: 49.5% female; N:339 for WC: 48.7% female; [underlined: Race/Ethnicity]:; N:362 for BMI: 55% Caucasian, 8.8% European, 3.6% Middle Eastern,; 5% Indian 3.9% Asian, 23.8% Undefined; N: 339 for WC:; 54.3% Caucasian, 8.8% European, 3.5% Middle Eastern,; 5% Indian 4.1% Asian, 24.2% Undefined; Background Diet:; N:362 for BMI: 41.7% BF ≥ 6mo; N:339 for WC: 42.2% BF ≥ 6mo | Quintiles of grams (g) and % total energy intake (%kcal) from CFB of core and extra foods at 18mo:; Dairy: combined milk and milk products: yogurt, cheese, ice cream, custard; Milk: skim, whole and evaporated; Fruit; Vegetables; Cereal: bread, pasta, rice, breakfast cereals, etc.; Meats: chicken nuggets, ground beef, beef sausages, ham, etc; Total extra foods: savory sauces, fats, and oils; Non-milk beverages: juice, cordial, fruit drinks and soft drinks; Sweetened drinks: cordial, fruit drinks and soft drinks;; Fried potatoes; Salty snacks: potato crisps, cheese snacks, corn chips; Confectionary: e.g., chocolate, jellies, energy bars; Cereal-based products: e.g., cookies, cakes, pies, buns; Age:18mo; Assessment Methods; Food record, 3d, weighed | Body composition; WC; Age: 8y; Assessment Methods; Body composition: BMI calculated from measured weight and length using kg/m2; Weight: electronic bathroom scale; to 1kg; Length: portable stadiometer to 1cm; WC: flexible, steel tape below costal border and iliac crest to 0.1cm; Measurements made by study nurses | [underlined: Confounders accounted for:]; Education: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X; Gestational age:X; Other: Parent obesity; smoking; daycare; n3 v. n6 group; Maternal and Gestational age were removed from model; [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine whether outcome assessors were blinded; Did not account for high attrition rate/lost to follow-up (22%); Did not adjust for potential key confounders (SES); Study was not powered to detect differences in obesity outcomes; Did not measure physical activity; Did not calculate intake from total core foods but calculated, analyzed, and reported intake from total extra foods
Garden, 2012; Prospective Cohort Study; Australia; [underlined: Sample Size]:; Baseline N: 616; Analytic N: 370 (at 3mo, Timing) Analytic N: 298 (at 18mo, Type); Attrition: 40% (3mo); Attrition: 51.6% (18mo); Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 49% female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 40% BF 0-3mo; 16.8% BF 3-6mo; 43.2% BF ≥6mo | Grams (g) and % total energy intake (%kcal) from CFB at 18mo:; Dairy: combined milk and milk products: yogurt, cheese, ice cream, custard; Milk: skim, whole and evaporated; Fruit; Vegetables; Cereal: bread, pasta, rice, breakfast cereals, etc.; Meats: chicken nuggets, ground beef, beef sausages, ham, etc.; Total extra foods: savory sauces, fats, and oils; Non-milk beverages: juice, cordial, fruit drinks and soft drinks; Sweetened drinks: cordial, fruit drinks and soft drinks;; Fried potatoes; Salty snacks: potato crisps, cheese snacks, corn chips; Confectionary: e.g., chocolate, jellies, energy bars; Cereal-based products: e.g., cookies, cakes, pies, buns; Age: 3mo; 18mo Assessment Methods; Questionnaire; Food record, 3d, weighed | Body composition; Age: 0-11.5y; Assessment Methods; Body composition: BMI trajectory calculated in kg/m2 based on measured weight and height (weight, electronic bathroom scale to 1kg; length: portable stadiometer to 1cm); categorized using CDC %tile curves for BMI:; Normal: tracks at 50th; Early and Persistent: at 75th at 2y crossing to 95th at 11.5y; Late Increase: tracks at 50th at 2y; crossed to 85th at 8y, and 90th at 11.5y; Measurements made by study nurses at 1, 3, 6, and 9mo; every 6mo from 9mo-5y, at 8y, at 11.5y; WC measured but NR | [underlined: Confounders accounted for:]; Education: X; Sex: X; Race/ethnicity: X; Feeding practices: X; Other: n3 vs. n6 intervention group; parent obesity; smoking; [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine whether outcome assessors were blinded; Did not account for high attrition rate/lost to follow-up (40%); Did not adjust for potential key confounders (SES, maternal age, birth size, gestational age)
Golley, 2013; Prospective Cohort Study; United Kingdom; [underlined: Sample Size]:; Baseline N: 13,978; Analytical N: 7y: 7834; 8y: 7170; Attrition: 7y: 44%; 8y: 48.7%; Power: NR; [underlined: Sex:]; 48.3% female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; Dietary pattern scores from FFQ collected at 7y; CFUI scores were negatively associated with a ‘‘processed’’ dietary pattern but positively associated with a ‘‘health conscious’’ dietary pattern | Each infant received a complementary feeding utility index (CFUI) score at 6mo, which was derived and analyzed as a continuous variable from 14 components (BF duration, age of introduction to solids, textured foods, and minimizing ready-made infant foods. Higher CFUI scores reflected higher adherence to CF guidelines.; Dietary patterns were not analyzed in relation to growth outcomes.; Age: 6mo; Assessment Methods; CFUI calculation from FFQ-derived dietary patterns | [underlined: Outcomes:]; Body composition; WC; Age: 7.5y; Assessment Methods; Body composition: BMI calculated from measured height/weight (stadiometer/Tanita scale); WC: flexible tape to the nearest 1mm | [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X (CFUI score); Birth size: X; Gestational age: X; Other: marital status, maternal smoking, maternal weight status, other children, singleton/twin and stimulating in the home environment; Model 2: height; [underlined: Limitations:]; Cannot determine validity/reliability of assessment for exposure; Cannot determine whether outcome assessors were blinded; Did not account for high attrition rate/lost to follow-up (44%); Race/ethnicity NR in article (collected in parent cohort) but adjusted for analyses
Hertrampf, 1990; Prospective Cohort Study; Chile; [underlined: Sample Size]:; Baseline N: 239; Analytic N: 189 at 4mo; 187 at 12mo; Attrition: 20.9% at 4mo; 21.7% at 12mo; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; 100% Hispanic; [underlined: Background Diet]:; All were BF at 3mo; When BF stopped, infants fed non-fortified whole cow’s milk | Fe-fortified cereal ~3-6mo: received 20g/d at 4mo and 40g/d at 6mo (100g: 360kcal, 11.6g pro, 0.3g fat, 14mg Fe); Control 3-6mo: routine CFB (at 3mo, fruit, cereal, juice; at 4mo, veg and meat; at 6mo, legumes and eggs); Age:4-6mo; Assessment Methods; NR | Weight; Age: 8mo, 12mo; Assessment Methods; Weight: weight/age adequacy as % median of NCHS standard for weight/age ratio | [underlined: Confounders accounted for:]; NSD in birth weight, BF duration, maternal age, or SES; [underlined: Limitations:]; Cannot determine group allocation methods; Cannot determine whether outcome assessors or investigators were blinded; Participants were not blinded to intervention status; Cannot determine reliablity/validity of outcome assessment (NR); Did not account for high attrition rate (~21%); Cannot determine adequacy of statistical methods (lack of detail)
Hoffman, 2004; Randomized Controlled Trial; United States; [underlined: Sample Size]:; Baseline N: 55; Analytic N: 51; Attrition: 93%; Sample Size Calculation/Power Analysis: N:21 to detect a 1SD difference in visual acuity, (stereoacuity, and blood lipids) at 12mo; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; All EBF to 9.7mo in control infants and to 8.8mo in DHA-rich infants; 65% of control infants, and 80% of DHA-rich infants were weaned to IF before 12mo | DHA-enriched CFB: receive 1 jar/day of solid baby food, enriched with DHA from egg-yolk, from 6 to 12mo; Control CFB: receive 1 jar/day of solid baby food from 6 to 12mo; CFB: solid baby food w/ and w/o DHA from egg yolk; DHA-rich food was 2.3 kJ/g higher in energy density than control food; 216 food jars in 5 varieties (vegetable, cereal w/ fruit, fruit custard) were shipped to participants; Age:6-12mo; Assessment Methods; Baby food jars weighed to ensure adherence and intake at 1-2mo | Body composition; Weight; Length; HC; Age: 6, 9, and 12mo; Assessment Methods; Body composition: Skinfold z-score; Weight: z-score; Length: z-score; HC: z-score; (Birch, 1998: Weight was measured using a Healthometer pediatric strain gauge scale accurate to 1g. Length was measured using Ellard Length Boards accurate to 0.1cm. Head circumference was measured using a nonstretching tape accurate to 0.1cm. Subscapular and triceps fat deposition were measured using a Lafayette skin fold caliper accurate to 1mm) | [underlined: Confounders accounted for:]; Feeding practices: All EBF; Gestational age: All full-term; [underlined: Limitations:]; Cannot determine investigators or outcome assessors were blinded
Iannotti, 2009; Prospective Cohort Study; Peru; [underlined: Sample Size]:; Baseline N: 579; Analytic N: 232; Attrition: 59%; Power Analysis: NR; [underlined: Sex:]; 49.1% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 92% BF during 6-12mo | Infants categorized as receiving CFB or animal source foods (meat, fish, egg, or milk) if the mother reported consumption of solid foods (cereal, meat or fish, mixed or blended foods, stews, bread or other cereal products, and purées) plus breastmilk. Number of observed days that food was consumed was divided by number of observation days.; Age: 6-12mo; Assessment Methods; Maternal report | Body composition; Weight; Length; HC; MUAC; Age: 1-12mo (monthly); Assessment Methods; Body composition: Skinfold thickness: calipers; MUAC, chest, and calf circumferences measured; Weight: Seca scale to 10g; converted to z-score; Length: measuring board to 0.1cm; converted to z-score; HC: measured | [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Feeding practices: X; Birth size: X; Other: Similar SES; Maternal education NS; [underlined: Limitations:]; Cannot determine whether groups were similar at baseline; Cannot determine if outcome assessors were blinded; Did not adjust for potential key confounders (maternal age, race/ethnicity, gestational age)
Kalies, 2005; Prospective Cohort Study; Germany; [underlined: Sample Size]:; Baseline N = 3,036; Analytic N = 2,337; Attrition = 23%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 49% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; Feeding mode during time of observation: 24.4% EBF first 0-1mo, 16.3% BF for 2-3mo, 20.8% BF for 4-5mo, 38.6% BF > or = 6mo. | CFB categorized as: self-made, ready-made, or mixture from both; Age:2y; Assessment Methods; Caregiver questionnaire | Weight, weight gain; Age: 24mo; Assessment Methods; Height, weight: recorded at preventive medical check-ups Risk of elevated weight gain at 24mo | [underlined: Confounders accounted for:]; SES: X; Sex: X; Feeding practices: X; Other: Smoking; maternal BMI; birth order; study center; All full-term; [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine if outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment (height and weight non-duplicate at medical check-ups); Did not account for high attrition rate (23%); Did not adjust for potential key confounders (education; maternal age; race/ethnicity); Parent self-reported feeding data; primary objective of study was not timing/type of CFB as such it appears IV/Exposure was used as a confounding in models
Kramer, 2004; Prospective Cohort Study; Belarus; [underlined: Sample Size]:; Baseline N: 17,601; Analytic N: 17,046; Attrition: 3%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; NR; 100% were BF at birth | Age of CFB introduction: based on intake at the start of the respective growth interval CFB: cereals, other solids, and juices; Age: 0-12mo; Assessment Methods:; Maternal interview | Body composition; Weight; Length; HC; Age: 1-3mo; 3-6mo; 6-9mo; 9-12mo; Assessment Methods:; Body composition: WLZ based on CDC/WHO, 2000; Weight: NR; used to calculate WAZ; Length: NR; used to calculate LAZ; HC: NR | [underlined: Confounders accounted for:]; Education: X; Birth size: X (All with birth weight >2.5kg); Gestational age: All full-term; Other: Anthropometric outcome at current time (WAZ, LAZ, WLZ, HC), geographic region, urbanicity, hospital; [underlined: Limitations:]; Cannot determine whether groups were similar on baseline characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment (unstandardardized); Did not adjust for potential key confounders (SES, sex, maternal age, race/ethnicity though participants were from RCT); Cereals consumed may not be generalizable; Only 1.2% of infants were consuming cereals at 3mo; Cannot rule out reverse causality, residual confounding, and selection bias; Trial promoted breast-feeding; Outcome assessment was unstandardized (various methods used; not primary outcome of original RCT)
Krebs, 2006; Randomized Controlled Trial; United States; [underlined: Sample Size]:; Baseline N: 88; Analytic N: 72; Attrition: 18.2%; Sample Size Calculation: N=100 to detect differences of 0.85 or more in weight-for-length z scores; [underlined: Sex:]; 51.1% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; All infants were EBF and receiving no routine vitamin or mineral supplements at enrollment; Formula use was minimal before 7mo; by 9 and 12mo (14 infants in each group) were consuming formula, averaging 8 to 9oz/d | Meat: Received pureed beef (Gerber Beef and Beef Gravy, Second Foods) from 5-7mo; Cereal: Received Fe-fortified cereal from 5-7mo (Gerber Fe fortified infant rice cereal, without Zn, First Foods), mixed with either expressed human milk or water on approximately a 1:2 ratio of cereal to fluid; Both groups were encouraged to wait until 5 mo to introduce the CFB, remained on their assigned food (with fruits and vegetables as desired after 1mo, avoiding the alternate study food) until 7 mo, when they could liberalize their diet to all foods; Age:5-7mo; Assessment Methods; Diet record, 3d | Body composition; Weight; Length; HC; Age: Baseline, 4-7mo; 7-12mo; 4-12mo for WAZ and LAZ; Assessment Methods; Body composition: WLZ from measured weight/length; Weight: gain and WAZ; electronic scale to 1g; Length: gain and LAZ; infant stadiometer to 0.1cm; HC: laminated tape; WAZ, LAZ, WLZ reported but data not shown | [underlined: Confounders accounted for:]; Sex: X; Birth size: X; Gestational age: X; [underlined: Limitations:]; Cannot determine whether group allocation was concealed; Participants were not blind; Cannot determine whether investigators and outcome assessors were blinded; Duration/length of follow-up differed because subjects started the intervention at different time points (e.g., only 22 infants (7 meat, 15 cereal) had started CFB at the 5mo visit); *Intake of protein and Zn at 7mo significantly predicted HC growth from 7-12mo in univaiate analyses
Krebs, 2013; Randomized Controlled Trial; United States; [underlined: Sample Size]:; Baseline N: 45; Analytic N: 41; Attrition: 8.9%; Sample Size Calculation: N= 15 per group to detect a 0.20mg difference in total absorbed Zn; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; EBF: 100%, all infants | Meat: Received one jar (71g) pureed meat and gravy per d by 7mo and >1 to ≤2 jars/d by 9mo; Fe-Zn Fortified Cereal: Received Fe and Zn fortified cereal, offer 1 serving/d (15g dry weight according to the manufacturer’s label) by 7mo and 2 servings/d by 9mo; Fe-Fortified Cereal: Received Fe-fortified cereal, offer 1 serving/d (15g dry weight according to the manufacturer’s label) by 7mo and 2 servings/d by 9mo; Fruits, vegetables, teething biscuits, and unfortified cereals and other finger foods were allowed ad lib. Cereal groups were instructed to avoid single-ingredient meats; at 8 mo, commercial infant dinners were allowed. Meat group instructed to avoid fortified infant cereals but was allowed to use unfortified cereals such as quick oats or commercial unfortified cooked rice starting at 7mo (≤15 g/d).; Age: 6-9mo; Assessment Methods; Food record, 3d | Weight; Length; Age: 7, 8, 9mo; Assessment Methods; Weight: naked; electronic digital balance to 1g in duplicate; Length: infant stadiometer to 0.1cm in duplicate | [underlined: Confounders accounted for:]; [underlined: Limitations:]; Cannot determine whether group allocation was concealed; Participants were not blinded; Cannot determine if investigators or outcome assessors were blinded; Infants were allowed ad lib feeding for foods other than those assigned (e.g., fruits and vegetables), and dietary intake was not accounted for; Multiple comparisons not adjusted for
Libuda, 2015; Randomized Controlled Trial; Germany; [underlined: Sample Size]:; Baseline N: 214; Analytic N: RBC fatty acids: 158; Plasma fatty acids: 155; Attrition: RBC fatty acids: 26.2%; Plasma fatty acids: 27.6%; Sample Size Calculation: N=63 to detect a 0.33% difference in RBC-DHA phospholipids; [underlined: Sex:]; ~50% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; ~58% BF, ~16% mixed feeding, ~26% FF | Rapeseed oil (ALA): Received CFB with ALA-rich rapeseed oil from 4-10mo; Fish (DHA): Received CFB as salmon 2/wk to provide preformed DHA from 4-10mo; Corn oil (Linoleic Acid): Received CFB with linoleic acid-rich corn oil from 4-10mo; Study foods were commercial meals with vegetables, potatoes, and meat (Rapeseed oil, Corn oil) or fish (Fish); Age:4-10mo; Assessment Methods; Diet record, weighed | Weight; Length; Age: 10mo; Assessment Methods; NR | [underlined: Confounders accounted for:]; Groups did not differ at baseline on SES, sex, feeding practices, maternal age, birth size or gestational age; [underlined: Limitations:]; Fish group (IG-F) not able to be blinded; Cannot determine whether adherence to study protocol was similar across groups; Cannot determine whether outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment; Did not account for high loss to follow-up (>20%)
Lind, 2004; Randomized Controlled Trial; Sweden; [underlined: Sample Size]:; Baseline N: 300; Analytic N: 263; Attrition: 12%; Sample size calculation: n=58-84 per group at 80% power with a=0.05 to detect differences in length of 0.9cm, 0.4kg; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; NR (BF or FF) | CC group: commercial MCD and porridge; MCD was oat and wheat flour, mixed with milk powder and Fe-fortified; PR group: phytate-reduced MCD and phytate-reduced porridge; MCD was replaced with white-wheat flour; IF group: milk-based infant formula and porridge; Age: 6-12mo; Assessment Methods; NR | Weight; Length; HC; MUAC; Age: 6, 12, and 18mo; Assessment Methods; Weight: measured on Seca scale in triplicate to 0.02kg; used to calculate WAZ; Length: measured on infantometer in triplicate to 1mm; used to calculate LAZ;; HC and MUAC: measured via non-stretchable tape to 1mm | [underlined: Confounders accounted for:]; Other: NR; [underlined: Limitations:]; Cannot determine whether groups differed at baseline on key characteristics; Cannot determine adherence to study protocols; Cannot determine impact of unintended exposures (partcipants allowed to consume anything from 12-18mo)
Liu, 1993; Randomized Controlled Trial; China; [underlined: Sample Size]:; Baseline N: 226; Analytic N: 164; Attrition: 27.4%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 45% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; Most were partially BF | Fortified Rusk: received 1 biscuit/day for 3mo (presumed to be fortified with iron, zinc, vit. A, calcium, and folic acid); Unfortified Rusk: received 1 unfortified biscuit/day for 3mo; CFB: Rusks were biscuits made from wheat flour, sugar, and vegetable oil; Age:6-16mo; Assessment Methods; Doctors ensured delivery of weekly rusk supply; mothers monitored child intake | Weight; Length; Age: 9-16mo; Assessment Methods; Weight: Beam balance; Length: length board | [underlined: Confounders accounted for:]; [underlined: Limitations:]; Cannot determine group allocation sequencing or concealment methods; Cannot determine whether investigators, participants, or outcome assessors were blinded; Cannot determine validity/reliability of outcome assessment; Cannot determine influence of background or usual diet on growth outcomes; Didnot adjust analyses for sex, which was unbalanced across groups; Limited generalizability due to sample from rural villages with high-rates of malnutrition
Lonnerdal, 1990; Randomized Controlled Trial; China; [underlined: Sample Size]:; Baseline N: NR; Analytic N: NR; Attrition: CD; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; 100% FF | Group A: Fed formula A w/o cereal; continued exclusive use of formula from 4-7mo; Group D: Fed formula A with 25g/d cereal from 4-7mo; Other groups confounded by formula:; Formula B+ Cereal: Fed formula B and 25g/d cereal from 4-7mo; Formula C+ Cereal: Fed formula C and 25g/d cereal from 4-7mo; Age:4-7mo; Assessment Methods; Trained nurses assisted mothers in weighing a/o recording intake of infant at home visits | Body composition; Weight; Length; HC; Age: 4, 5, 6, and 7mo; Assessment Methods; Weight, length, and HC measured at clinic; Weight-for-height: calculated from measures; Skinfold thickness: NR | [underlined: Confounders accounted for:]; Other: NR; [underlined: Limitations:]; Cannot determine group allocation or randomization methods; Cannot determine whether groups were similar on baseline characteristics; Cannot determine validity/reliability of outcome assessment; Cannot determine attrition because sample size was not reported; Did not adjust for other sources of bias; Adequacy of statistical methods insufficient Lack of reporting on sample size, characteristics, IV/Exposure assessment
Makrides, 1998; Randomized Controlled Trial; Australia; [underlined: Sample Size]:; Baseline N High-Fe Group: 40; Baseline N Control Group: 39; Analytic N High-Fe Group: 36; Analytic N Control Group: 26; Attrition: 22%; Sample Size Calculation: N=60 to detect differences of 6g/L in Hb and 18mg/L in SF; [underlined: Sex:]; 50% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; EBF: 100% at 6mo; BF: 100% through 9mo | High-Fe weaning diet: Offered four 30-40g servings/wk of red meat and four 113g jars/wk of Fe-fortified cereal; Control: Standard nutritional advice (including advice to consume iron-fortified infant cereal from 4 to 6mo); Age: 6-12mo; Assessment Methods; FFQ (for iron-containing foods) | Weight; Length; HC; Age: 9mo, 12mo; Assessment Methods; Weight: Measured by study personnel; Length: Measured by study personnel, supine to nearest 0.5cm; HC: Measured by study personnel, to nearest 0.1cm | [underlined: Confounders accounted for:]; Feeding practices: X (All EBF); Birth size: X (All >2500g); Gestational age: X (All >37wk); [underlined: Limitations:]; Cannot determine if group allocation was concealed; Participants were not blinded; cannot determine if outcome assessors or investigators were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., single vs multiple growth measures); Statistical analyses not described and data not shown
Makrides, 2002; Randomized Controlled Trial; Australia; [underlined: Sample Size]:; Control Baseline N: 28 (BF), 27 (FF); Regular Egg Baseline N: 27 (BF), 26 (FF); N-3 Egg Baseline N: 27 (BF(, 26 (FF); Control Analytic N: 23 (BF), 23 (FF); Regular Egg Analytic N: 23 (BF), 24 (FF); N-3 Egg Analytic N: 24 (BF, 20 (FF); Attrition: 15%; Power Analysis/Sufficient Sample Size: N=40 per egg group, N=20 in control to detect differences in iron status outcomes (8g/L (SD=10) in Hb and 20g/L (SD=25) in SF).; [underlined: Sex:]; 53% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF: 51% | Regular egg group: Provided 4 eggs/wk from 6 to 12mo; N-3 egg group: Provided 4 DHA enriched eggs/wk from 6 to 12mo; Control group: Followed standard weaning diet of choice from 6 to 12mo; Age: 6-12mo; Assessment Methods; Maternal questionnaire | Weight; Length; HC; Age:12mo; Assessment Methods; Weight: NR; Length: NR; HC: NR | [underlined: Confounders accounted for:]; Feeding practices: X; Birth size: X (All >2500g); Gestational age: X (All >37wk); [underlined: Limitations:]; Cannot determine validity/reliability of outcome assessment (methods were not described)
Morgan, 2004; Prospective Cohort Study; United Kingdom; [underlined: Sample Size]:; Baseline N: 144; Analytic N: 144; Attrition: 0%; Power Analysis: NR; [underlined: Sex:]; 47% Female; [underlined: Race/Ethnicity]:; 97% White; [underlined: Background Diet]:; Ever BF: 83%; BF at 4mo: 37%; BF at 6mo: 2% | Meat intake: Total grams of red (beef, pork and lamb) and white (chicken, turkey, fish) meat consumed from 4-12mo and from 4-16mo; Median for all infants >20mo: 278g/d (178-425g/d); Age: 4-12mo, 4-16mo, 4-24mo; Assessment Methods; Food record, 7d, weighed | Weight; Length; HC; Age: 4, 8, 12, 16, 20 and 24mo; Assessment Methods; Weight: Measured in duplicate or triplicate by study personnel, to nearest 10g; Length: Measured in duplicate or triplicate by study personnel, supine to nearest 1mm; HC: Measured in duplicate or triplicate by study personnel | [underlined: Confounders accounted for:]; Feeding practices: X; Birth size: X; Other: Energy intake, protein intake; [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine if outcome assessors were blinded; Did not adjust for potential key confounders (education, SES, sex, maternal age, race/ethnicity or gestational age)
Olaya, 2013; Randomized Controlled Trial; Colombia; [underlined: Sample Size]:; Baseline N: 85; Analytic N: 76; Attrition: 11%; Sample Size Calculation: N=64 per group to detect a 0.5SD difference in outcomes; [underlined: Sex:]; 50% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; EBF: 100% at 4mo; At 6mo: 8% >11 bottle-feed/d, 7% consuming cow’s milk; Age of introduction to CFB: 45% between 4-6mo; 30% consumed red meat at 6mo | Intervention group: Received individual, face-to-face nutrition counseling with 3 key messages: the importance of continuing BF alongside CF, red meat as a source of Fe to prevent anemia (>5 portions/wk, red meat, chicken liver and heart), and daily fruit and vegetables as part of a healthy diet; Control group: Received standard complementary feeding advice from health care professionals (including meat consumption, but no advice on frequency or amount of foods was given); CFB: At 12mo, the Intervention group consumed more meat, red meat, fruit, vegetables, and legumes, while the Control group was more likely to consume follow-on formula, milk, cow milk, and sweetened foods (sugar, jelly, chocolate, sweets); Age: 6-12mo; Assessment Methods: FFQ | Weight; Length; HC; MUAC; Age: 12mo; Assessment Methods; Weight: Measured by study personnel; z scores determined using WHO, 2007 standards; Length: Measured in triplicate by study personnel, recumbent to nearest 1mm; z scores determined using WHO, 2007 standards; MUAC: Measured by study personnel to nearest 1mm; HC: Measured by study personnel to nearest 1mm | [underlined: Confounders accounted for:]; SES: X; Sex: X; Other: Baseline growth measures; [underlined: Limitations:]; Groups differed at baseline on key characteristics and differences were not adjusted for in analyses (father’s age, baseline weight, baseline MUAC); Despite intervention, control and intervention groups consumed similar CFB; Participants were not blinded; cannot determine if outcome assessors or investigators were blinded
Robinson, 2009; Prospective Cohort Study; United Kingdom; [underlined: Sample Size]:; Baseline N: 1195; Analytic N: 536; Attrition: 55%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 47% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; Never BF: 12.5%; BF for 6mo: 20%; Age of introduction to CFB: 76% by 4mo | One dietary pattern was identified at 12mo using principal component analysis, and each infant received a score for adherence to the pattern:; Infant guidelines pattern: High consumption of fruit, vegetables, cooked meat and fish, and other home-prepared foods (rice, pasta), and low consumption of commercial baby foods; Age: 6 and 12mo Assessment Methods; FFQ; maternal interview | Body composition; Age: 4y; Assessment Methods; Body composition:; - BMI: Calculated using measured height, weight; - Lean mass (LM): Whole-body DXA; - LM index: lean mass divided by height2; - Fat mass (FM): Whole-body DXA; - FM index: FM divided by height 2 | [underlined: Confounders accounted for:]; SES: X; Maternal age: X; Feeding practices: X; Birth size: X; Other: Maternal BMI, maternal height, smoking in late pregnancy; [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of some outcome measures (i.e., single vs multiple height, weight measures); Did not define age of introduction of CFB variable; Did not account for high loss to follow-up (55%); Did not adjust for potential key confounders (education, sex, race/ethnicity, gestational age)
Rose, 2016; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N: 1807; Analytic N: 1029; Attrition: 43%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 51% Female; [underlined: Race/Ethnicity]:; ~90% White; [underlined: Background Diet]:; BF at 9mo: ~34%; Age of introduction to CFB: ~5mo | Five dietary patterns were identified at 9mo using latent class analysis, and each infant was assigned to the pattern they scored highest on:; 1. BFFV: Breastfed Fruits and Vegetables: Breastmilk, fruits, and vegetables, and low intake of energy-dense foods; 2. BFLV: Breastfed Low Variety: Breastmilk, and low intake of fruits and vegetables, low diet variety; 3. FFFV: Formula-Fed Fruits and Vegetables: Formula, fruits, and vegetables, and low intake of energy-dense foods; 4. FFLV: Formula-Fed Low Variety: Formula, and low intake of fruits and vegetables, low diet variety; 5. MXHED: Mixed High Energy Density: Breastmilk and formula, low intake of fruits and vegetables, diet variety, and higher intake of energy-density foods (e.g. French fries, sweet foods); Age:9mo; Assessment Methods FFQ | Weight status; Body composition; Weight; Age: 1y; Assessment Methods; Weight status: prevlance of overweight classified as ≥85th WFL percentile; WFL calculated using maternal-reported weight and length; Body composition: WLZ; Weight: WAZ; maternal-report | [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X; Gestational age: X; Other: Childcare, parity, prepregnancy BMI, marital status, postpartum depression, excessive gestational weight gain; [underlined: Limitations:]; Outcome assessors were not blinded (maternal report); Did not use valid/reliable methods to measure outcomes (weight was self-reported by mothers); Did not account for high loss to follow-up (43%)’; Did not describe p-values for all analyses reported
Santorelli, 2014; Prospective Cohort Study; United Kingdom; [underlined: Sample Size]:; Baseline N: 1735; Analytic N: 1327; Attrition: 24%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; 38% White, 49% Pakistani, 7% South Asian, 6% Other; [underlined: Background Diet]:; BF after CFB introduction: 32%; Age of CFB introduction: 10% <17wk | Age of non-sweetened solid foods (e.g. baby rice, pureed vegetables, fruits or rice, and lentils/dhal); sweetened foods (e.g. egg custard, rice pudding, sweetened rusks, biscuits and cake) were introduced as a first food: whether sweetened foods were introduced as a first food (including sweetened and nonsweetened foods given together);; Sweetened drinks (e.g. cola, squash, lemonade, sweetened tea and pre-prepared ‘baby’ drinks) given at <17wk of age; Age: 6, 12mo; Assessment Methods; Maternal questionnaire | Body composition; Age: 3y; Assessment Methods; Body composition: BMIZ, calculated via measured height, weight and converted into age- and sex-adjusted z-scores based on WHO, 2006 growth standards | [underlined: Confounders accounted for:]; Education: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X; Birth size: X; Gestational age: X; Other: Marital status, smoking during pregnancy, maternal BMI, delivery mode; [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome measures (i.e., single vs multiple growth measures); Did not account for high loss to follow-up (24%); Did not adjust for potential key confounders (SES)
Schack-Nielsen, 2010; Prospective Cohort Study; Denmark; [underlined: Sample Size]:; Baseline N: 8129; Analytic N: 5068; Attrition: 39%; Power Analysis/Sample Size Calculation: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF duration: 3.5mo; BF <2wk: 18%; Age of CFB introduction: 3.8mo; 79% introduced to vegetables and spoon-feeding at the same age; 19% started spoon-feeding/gruel first | Age of introduction to CFB: Continuous, mo; Categorical, ≥4mo vs <4mo; Number of food items at 3, 4, 5, and 6mo; CFB: spoon-feeding (i.e., gruel), vegetables, eggs, meat, firm food; Age: 1y; Assessment Methods:; Maternal questionnaire | Weight status; Body composition; WC; Age: 1-42y; Assessment Methods:; Weight status: risk of overweight based on BMI ≥25 using self-reported height and weight at 42y; Body composition: BMI calculated using height, weight measured by study personnel at 1, 3, and 6y; school records at 7-14y; self-reported at 2-34y, 42y; WC: Self-reported at 42y via mailed questionnaire and tape measure | [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Feeding practices: X; Birth size: X (Birth weight); Gestational age: X; Other: Prepregnancy BMI, gestational weight gain, smoking during pregnancy, marital status, weight at 1y; [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Outcome assessors were not blinded at 20-34y, 42y; Did not use valid/reliable measures to assess outcomes (weight was self-reported at 20-34y and 42y); Did not account for high loss to follow-up (39%); Did not adjust for potential key confounders (race/ethnicity); Not all variables were analyzed in relation to all outcomes, and data from figures not adequately described; Limited generalizability due to CFB practices at the time of original data collection (1959-1960)
Schwartz, 2009; Randomized Controlled Trial; Germany; [underlined: Sample Size]:; Intervention Group Baseline N: 66; Control Group Baseline N: 66; Intervention Group Analytic N: 53; Control Group Analytic N: 49; Attrition: 23%; Power Analysis/Sufficient Sample Size: N=60/group to detect a 10% higher blood n-3 fatty acid levels with alpha of 0.05 and 95% power (SD of 12%).; [underlined: Sex:]; 50% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; EBF duration: 19wk; Age of CFB introduction: 21wk | Intervention Group: Received one jar/d (190g for 4-7mo, 220g for 7-10mo) for 4mo of a meat meal with rapeseed (canola) oil (LA 20%; ALA 9%; LA/ALA 2.2); LA/ALA ratio of 3.9; Control Group: Received one jar/d (190g for 4-7mo, 220g for 7-10mo) for 4mo of a meat meal with corn oil (LA 55% of total fatty acid; ALA 1%; LA/ALA 55); LA/ALA ratio of 35.7; Age: 6-10mo; Assessment Methods; Food record, daily | Weight; Age: 4-10mo; 10mo; Assessment Methods NR | [underlined: Confounders accounted for:]; Birth size: X (All >2.5kg); [underlined: Limitations:]; Cannot determine validity/reliability of outcome measures (methods not described); Did not account for high loss to follow-up (23%); Study was powered to detect differences in plasma fatty acids levels, so may not have been adequately powered to detect differences in growth
Sonneville, 2015; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N: 2128; Analytic N: 1163; Attrition: 45%; Power Analysis: NR; [underlined: Sex:]; 50% Female; [underlined: Race/Ethnicity]:; 70% White, 12% Black, 4% Hispanic, 3% Asian; [underlined: Background Diet]:; BF duration: 6.4mo | Juice intake (OJ, 100% fruit) servings/d: 0, 1-7, 8-15, 16-31, or >32 ounces; Age:1y; Assessment Methods; Maternal questionnaire | Body composition; Age: 3.1y, 7.7y; Assessment Methods; Body composition: BMIZ, calculated using measured height, weight, and converted to age- and sex-specific z-scores based on US reference growth data | [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Race/ethnicity: X; Other: Maternal age, prepregnancy BMI, child age, WLZ at 1y, caloric intake; [underlined: Limitations:]; Groups differed at baseline on BF duration, which was not adjusted for in analyses; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., single vs multiple growth measures); Did not account for high loss to follow-up (45%); Did not adjust for potential key confounders (feeding practices, birth size, gestational age); Did not distinguish between 100% fruit juice and non-100% fruit juice
Tang, 2014; Randomized Controlled Trial; China; [underlined: Sample Size]:; Baseline N: 1471; Analytic N: 1318; Attrition: 10%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; EBF: 100% at enrollment | Pork group: Received 60g/d of fresh, certified safe pork, to be boiled by the parents from 6-18mo; Cereal group: Received daily supplements of a commercially available or isocaloric packaged pressed rice cereal product from 6-18mo; Age: 6-18mo; Assessment Methods; Food diaries | Body composition; Weight; Length; HC; Age: 6mo, 7mo, 9mo, 12mo, 15mo, 18mo; Assessment Methods; Body composition: WLZ from measured weight/length; Weight: weight and WAZ, measured by study personnel, to nearest 5g; Length: Measured by study personnel, to nearest 0.1cm; HC: NR | [underlined: Confounders accounted for:]; Education: X; SES: X; Feeding practices: X (all EBF); Gestational age: X (all full term); Other: Maternal height and weight, baseline length; [underlined: Limitations:]; Cannot determine whether group allocation was concealed; Cannot determine whether adherence was similar between groups; Participants were not blinded; cannot determine whether investigators or outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., single vs multiple growth measures)
Tang, 2014b; Randomized Controlled Trial; United States; [underlined: Sample Size]:; Baseline N: 45; Analytic N: 42; Attrition: 7%; Power Analysis and Sufficient Sample Size: NR for this secondary analysis. Authors do state that they had 50% and 60% power to test changes in LAZ and WAZ respectively.; [underlined: Sex:]; 60% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; EBF: 100% at enrollment | Meat group: Received one jar/d of pureed meat and gravy (71 g total, equivalent to 8 g protein) by 7mo of age and 1-2 jars/d by 9mo of age; Cereal group: Received 1 serving/d of cereal (15 g dry weight by manufacturer’s label, iron or iron-zinc fortified) by 7 mo of age and 2 servings/d by 9 mo of age; asked to avoid meats; Age: 5-9mo; Assessment Methods; Food records, 3d | Body composition; Weight; Length; WC; Age: 5, 6, 7, 8, 9mo Assessment Methods; Body composition: BMI and WLZ calculated via measured height, weight; Weight:WAZ, measured by study personnel, duplicate; Length: LAZ, ,easured by study personnel, to nearest 0.1cm, duplicate; WC: NR | [underlined: Confounders accounted for:]; Birth size: X (All appropriate for gestational age); Gestational age: X (All full term); [underlined: Limitations:]; Cannot determine whether group allocation was concealed; Participants and investigators were not blinded; cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., head, waist circumference)
Tantracheewathorn, 2005; Prospective Cohort Study; Thailand; [underlined: Sample Size]:; Baseline N: 156; Analytic N: 140; Attrition: 10%; Power Analysis and Sufficient Sample Size: N=156 to detect a 0.57kg (SD=1.16) difference in weight at 12mo with a power of 80%, pvalue of 0.05, and 20% loss to follow-up; [underlined: Sex:]; 50% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; BF: 50%, FF: 50% | Adequate complementary food: consumed a variety of food from various food groups (rice and grains, fruits, vegetables, milk, meat, eggs, fat), and adequate amounts of nutrient and energy compared with Thai Recommended Dietary Allowances; Age: Data collected at 1, 2, 4, 6, 9, 12mo, but cannot determine when CFB adequacy was assessed Assessment Methods; Parental interview, 24hr recall | Weight status; Age: Cannot determine; Assessment Methods; Weight status: malnutrition (Wasting, Stunting, Underweight) calculated using measured height, weight, defined by WAZ, LAZ, or weight-for-height z-score (WHZ) <2SD of the Thai references. | [underlined: Confounders accounted for:]; Feeding practices: X; Birth size: X (All>2500g); Gestational age: X (All 37-42wk); [underlined: Limitations:]; Cannot determine whether groups were similar at baseline on key characteristics; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome measures (i.e., single vs multiple measures); Did not adjust for key confounders (education, SES, sex, maternal age, race/ethnicity); Adequacy of statistical methods insufficient (unclear what time points were used to calculate the exposure and outcome variables)
Virtanen, 2001; Randomized Controlled Trial; Sweden; [underlined: Sample Size]:; Baseline N: 54; Analytic N: 36; Attrition: 33%; Sample Size Calculation: N=50 (25 in each group) to detect differences in Hb (4.0g/L) and TfR (0.8mg/L) concentration; [underlined: Sex:]; 67% Female; [underlined: Race/Ethnicity]:; 100% White; [underlined: Background Diet]:; All feeding according to current Swedish guidelines (BF at birth, and if not, fed Fe-fortified infant formula until 6mo; After 6mo of age all (except 3) fed Fe-fortified follow-on formula with meal) | Cow’s milk group: Received either low-fat or standard-fat cow’s milk, ad libitum; Iron-fortified cow’s milk groups: Received either Fe-fortified cow’s milk, fortified with ferrous gluconate-fortified cows milk with 50% of the fat being vegetable fat, or Fe-fortified cow’s milk, fortified with ferrous lactate-fortified cows milk with 100% of the fat being vegetable fat, ad libitum; Age:12-18mo; Assessment Methods; Food record, 7d | Weight; Age: 12-18mo; 18mo; Assessment Methods; Weight: absolute and change in weight; measured by study personnel, to nearest 5g | [underlined: Confounders accounted for:]; Race/ethnicity: X (100% white); [underlined: Limitations:]; Cannot determine the validity/reliability of outcome assessment (i.e., single vs multiple measures); Did not account for high loss to follow-up (33%); Author noted study may not have been adequately powered
Walter, 1993; Randomized Controlled Trial; Chile; [underlined: Sample Size]:; Baseline N: 515; Analytic N: 444 at 8mo, 370 at 12mo, 340 at 15mo; Attrition: 14% at 8mo, 28% at 12mo, 34% at 15mo; Power Analysis/Sample Size Calculation: NR; [underlined: Sex:]; NR; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; EBF: 100% at enrollment | FF infants were randomized to one of the following three groups:; Group 1: Received Fe-fortified cereal (30g/d) + unfortified formula; Group 2: Received unfortified cereal + unfortified formula; Group 3: Received unfortified cereal + fortified formula; BF infants were randomized to one of the following two groups:; Group 4: Fe-fortified cereal + breastmilk; Group 5: Unfortified cereal + breastmilk; Age: 4-15mo; Assessment Methods; Food record, daily, measured | Weight; Length; Age: 8, 12, 15mo; Assessment Methods; Weight: NR; Length: NR | [underlined: Confounders accounted for:]; Other:; [underlined: Limitations:]; Cannot determine whether group allocation was concealed; Cannot determine whether the groups differed at baseline on key characteristics; Cannot determine whether investigators or outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (methods not described); Did not account for high loss to follow-up (60%); Adequacy of statistical methods insufficient (statistical tests and p-values are not consistently provided)
Wen, 2014a; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N: 3033; Analytic N: 530; Attrition: 83%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 50% female; [underlined: Race/Ethnicity]:; 91% White, 1% African American, 3% Hispanic, 3% Asian/Pacific Islander; [underlined: Background Diet]:; NR | Four dietary patterns were identified using principal component analysis, and infants were assigned an adherence score to each pattern at 6mo:; Infant guideline solids: Baby cereal, fruit, vegetables, meat/chicken; High sugar/fat/protein: Sweet drinks, French fries, fish/shellfish, nut foods, eggs, sweet foods; High dairy/regular cereal: Cow’s milk, other dairy, 100% juice, non-baby cereals/starches; Formula: Formula, low intakes of breast milk; Age: 6mo; Assessment Methods; FFQ | Body composition; Length; Age: 6-12mo; Assessment Methods; Body composition: change in BMI, calculated using maternal report of weight/length; Length: Maternal report | [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Maternal age: X; Race/ethnicity: X; Feeding practices: X (other dietary pattern scores); Gestational age: X; Other: Growth at 6mo, pre-pregnancy BMI, gestational diabetes, gestational weigh gain; [underlined: Limitations:]; Dietary pattern adherence was associated with birth weight, which was not adjusted for in analyses; Outcome assessors were not blinded (maternal report); Did not use valid/reliable measures to assess outcomes (maternal report of infant weight, length); Did not account for high loss to follow-up (85%); Did not adjust for potential key confounders (birth size)
Wosje, 2001; Prospective Cohort Study; United States; [underlined: Sample Size]:; Baseline N: 121; Analytic N: 51; Attrition: 58%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 45% Female; [underlined: Race/Ethnicity]:; 94% White; [underlined: Background Diet]:; NR | Type of milk consumed: 2% vs. whole milk; Age:12mo; Assessment Methods; Food record, 3d | Body composition; Weight; Length; Age: 24mo; Assessment Methods; Body composition: % body fat via DXA; Weight: Measured by study personnel to 0.001kg; Length: Measured by study personnel, to 0.5cm, recumbent | [underlined: Confounders accounted for:]; [underlined: Limitations:]; Did not account for dietary intake aside from type of milk consumed; Cannot determine whether outcome assessors were blinded; Cannot determine the validity/reliability of outcome assessment (i.e., single vs multiple measures) ; Did not account for high loss to follow-up (58%); Did not adjust for key confounders (education, SES, sex, maternal age, race/ethnicity, feeding practices, birth size, gestational age)
Yeung, 2000; Randomized Controlled Trial; Canada; [underlined: Sample Size]:; Intervention Baseline N: 79; Control Baseline N: 77; Intervention Analytic N: 49; Control Analytic N: 54; Attrition: 34%; Sample Size Calculation: N=55 per group to detect differences in Fe depletion; [underlined: Sex:]; 48% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; All subjects in the intervention group were fed cow’s milk; in the control group, cow milk was delayed until 10mo | Intervention group: Received pureed meat (1-2 jars/d) and Fe-fortified infant cereals (2/3 c/d) from 6 to 12mo; all other foods allowed at parents’ discretion (except vitamin/mineral supplements containing Fe and Fe-fortified formulas); Control group: No dietary intervention; Age: 6-12mo; Assessment Methods; Parent questionnaire | Weight; Length; HC; Age: 8, 10, 12mo; Assessment Methods; Weight: Measured by study personnel, in triplicate; Length: Measured by study personnel, recumbent, in triplicate; HC: Measured by study personnel in triplicate | [underlined: Confounders accounted for:]; Gestational age: X (All full term); [underlined: Limitations:]; Participants and outcome assessors were not blinded; Did not account for high loss to follow-up (~34%)
Zheng, 2015; Prospective Cohort Study; China; [underlined: Sample Size]:; Baseline N: 90066; Analytic N: 40510; Attrition: 55%; Power Analysis and Sufficient Sample Size: NR; [underlined: Sex:]; 48% Female; [underlined: Race/Ethnicity]:; NR; [underlined: Background Diet]:; Ever BF: 93% | Age of CFB introduction: <3, 4-6, >6mo; CFB: fish liver oil, rice cereal/porridge, egg yolk, fish paste, liver paste, tofu, animal blood, bread/steamed bun/fine dried noodle, ground meat/soy product, and pureed noodle/cookies; Age: 1, 3, 6mo; Assessment Methods:; Maternal interview | Weight status; Body composition; Age: 4-5y; Assessment Methods:; Weight status: Obesity defined as BMI z-score>2SD, overweight defined as between 1-2SD; Body composition: BMI calculated using self-reported weight, height | [underlined: Confounders accounted for:]; Education: X; SES: X; Sex: X; Feeding practices: X (BF, timing of other CFB); Birth size: X (Birth weight); Gestational age: X; Other: Maternal menarcheal age, type of delivery, maternal BMI, maternal occupation, weight gain by 3mo, age of other children; [underlined: Limitations:]; Outcome assessors were not blinded; Did not use valid/reliable measures to assess outcomes (weight was self-reported; lack of detail provided); Did not account for high loss to follow-up (55%); Did not adjust for potential key confounders (sex, maternal age, race/ethnicity); Concern for multiple testing (analyzed two correlated outcomes [BMI, weight status] across many types of foods, increasing chance of false-positives; Cohort data collected over a long interval (1999-2009); Limited generalizability due to population having very low prevalence of obesity (<2%)