# List of abbreviations

Abbreviation: Full name
aBMC: Area-adjusted bone mineral content
BA: Bone area
BMC: Bone mineral content
BMD: Bone mineral density
CFB: Complementary food and beverages
FEG: Federal Expert Group
HHS: Department of Health and Human Services
NEL: Nutrition Evidence Library
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
P/B-24: Pregnancy and Birth to 24 Months Project
PTH: Parathyroid hormone
TEC: Technical Expert Collaborative
USDA: United States Department of Agriculture