# WHAT IS THE RELATIONSHIP BETWEEN TYPES AND/OR AMOUNTS OF COMPLEMENTARY FOODS/BEVERAGES AND BONE HEALTH?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between types and/or amounts of complementary foods and beverages and bone health?

### What is the answer to the question?

- Insufficient evidence is available to draw conclusions about the relationship between the types and/or amounts of complementary foods and beverages consumed and bone health.

### Why was this question asked?

- This important public health question was identified and prioritized as part of the U.S. Department of Agriculture and Department of Health and Human Services Pregnancy and Birth to 24 Months Project.

### How was this question answered?

- A team of Nutrition Evidence Systematic Review staff conducted a systematic review in collaboration with a group of experts called a Technical Expert Collaborative

### What is the population of interest?

- Generally healthy infants and toddlers who were fed complementary foods and beverages from ages 0-24 months and had bone health examined through 18 years of age.

### What evidence was found?

- This review includes 2 studies.
- These studies examined the dietary patterns consumed by infants and bone health.
- Complementary foods and beverages are foods and beverages other than human milk or infant formula provided to an infant or young child.
- There are limitations in the evidence as follows: only a few studies were done, and they varied too much to be able to answer the question.

### How up-to-date is this review?

- This review includes literature from 1/1980 to 7/2016.

## FULL REVIEW

### Systematic review question

What is the relationship between types and/or amounts of complementary foods and beverages and bone health?

### Conclusion statement

Insufficient evidence is available to draw conclusions about the relationship between the types and/or amounts of complementary foods and beverages consumed and bone health.

### Grade

Grade Not Assignable

### Summary

- Complementary foods and beverages (CFB) were defined as foods and/or beverages (liquids, semisolids, and solids) other than human milk or infant formula provided to an infant or young child to provide nutrients and energy. Because fluid cow’s milk may serve as a substitute for, rather than a complement to, human milk or infant formula in the first year of life, only data for cow’s milk consumption between 12 and 24 mo of age were included in this systematic review. However, milk products, such as a cheese and yogurt, were considered as CFB. This review includes studies that examined the relationship between consuming different types and/or amounts of CFB and bone health during childhood.
- Two prospective cohort studies published since 1980 met the inclusion criteria for this review, both of which examined the relationship between infants’ and toddlers’ dietary patterns and bone health.
- The ability to draw conclusions about the relationship between the types and/or amounts of CFB consumed and bone health is limited by an overall lack of research.
- Although both cohort studies included in this review assessed dietary patterns at 12-13 months, in relationship to a single assessment of bone mineral content at 4 or 6 years of age, it is not possible to draw conclusions for types and/or amounts of CFB and bone health given the non-specific nature of the dietary patterns, as well as the long interval between the assessment of dietary pattern and radiological measurement of bone health.

### Description of the Evidence

Two prospective cohort studies, from the United Kingdom (U.K.) and the Netherlands, were included in the systematic review that examined the relationship between types and/or amounts of CFB consumed and bone health during childhood (through 18 y of age) (Table 2) (1, 2). Both studies examined the relationship between infant dietary patterns (derived using principal component analysis) and bone health.

Harvey et al. (1) examined adherence at 6 mo and 12 mo of age to the “Infant Guidelines Pattern”, which conformed to U.K. infant feeding guidelines (i.e., high frequency of consumption of vegetables, fruit, meat/fish, and home-prepared foods). Results showed no significant associations between degree of adherence to the Infant Guidelines Pattern at either 6 mo or 12 mo of age and areal BMD, volumetric BMD, BMC, or BA at 4 y (Table 3).

van den Hooven et al. (2) examined adherence at ~12.9 mo of age (range 12.2 to 19 mo) to 3 dietary patterns:

- Dairy and Whole Grains Pattern: higher intakes of whole grains, dairy, cheese, and eggs, and lower intakes of human milk and infant formula
- Potatoes, Rice, and Vegetables Pattern: higher intakes of potatoes, pasta, rice, vegetables, meat, meat products, fish, shell-fish, oils, condiments, and sauce
- Refined Grains and Confectionery Pattern: higher intakes of refined grains, solid fats, confectionery, snack bar products, savory snacks, and sugar-containing beverages

Results showed that higher adherence to the Dairy and Whole Grains Pattern at ~13 mo was associated with higher BMD and aBMC at 6 y; but no associations were found with the Potatoes, Rice, and Vegetables Pattern or Refined Grains and Confectionery Pattern. Further analyses showed that among those who did not receive vitamin D supplements at 14 mo, adherence to the Dairy and Whole Grains Pattern was associated with higher aBMC, but lower BA. Among those who did receive vitamin D supplements, there were no associations between dietary pattern scores and any measure of bone health.

### Evidence synthesis

Only 2 prospective cohort studies published since 1980 met the inclusion criteria for the systematic review on types and amounts of CFB consumed and bone health, both of which examined infants’ and toddlers’ dietary patterns. The dietary patterns examined in each study differed in terms of the combinations of foods and food groups included, making it difficult to compare and contrast the results of the studies. Furthermore, both studies examined dietary patterns in infancy (6-12 mo of age) or in early toddlerhood (~13 mo) and looked at bone health outcomes that occurred several years later at 4 y or 6 y of age, and did not account for changes in dietary patterns that likely occurred during the follow-up time period.

Therefore, it is difficult to draw conclusions as to whether the types or amounts of CFB consumed impact bone health.

### Research recommendations

Given that evidence was insufficient to draw conclusions, additional research is needed to determine whether the age at which complementary feeding begins impacts bone health later in life. This includes research that addresses key gaps and limitations in the evidence, such as:

- Well-conducted and adequately powered studies that focus on CFB containing nutrients that are likely to impact bone health that are likely to impact bone health.
- Accounting for whether infants were fed breastmilk and/or infant formula, and other aspects of the overall diet quality consumed from the time at which CFB are introduced to the time when bone health is assessed, including whether infants received vitamin D supplements.
- Adjusting for key confounding factors in observational studies, including: education, socioeconomic status, race/ethnicity, child sex, gestational age, birth weight, growth pattern (or status), diet quality and vitamin D and calcium intake, sunlight exposure, and physical activity.
- Including diverse populations with varying racial/ethnic and socioeconomic backgrounds.
- Including sufficient duration of follow-up, through the second year of life and into childhood, to assess the longer-term effects of complementary feeding on bone health, including functional outcomes (i.e., risk of fracture).

Table 1 Description of evidence on types and/or amounts of complementary foods and beverages (CFB) and bone health

Reference; study design; n; country | Exposures | Results
Harvey, 2009 (1); Prospective Cohort Study; n= 599; United Kingdom | Infant Guidelines Pattern (vegetables, fruit, meat/fish, and home-prepared foods): Adherence scores at 6 and 12mo | Bone area (BA), bone mineral content (BMC), bone mineral density (BMD), volumetric BMD at 4y: No significant associations with dietary patterns
van den Hooven, 2015 (2); Prospective Cohort Study; n = 2,850; The Netherlands | Dairy and Whole Grains Pattern (higher whole grains, dairy, cheese, eggs; lower human milk, infant formula): Adherence scores at 13mo by quartiles (Q), with Q 4 representing highest adherence | BMD at 6y, Q4 vs. Q1, 3.98 mg/cm2, 95% CI 0.36, 7.61, P<0.05
van den Hooven, 2015 (2); Prospective Cohort Study; n = 2,850; The Netherlands | | BA at 6y in subjects receiving vitamin D supplements at 14mo: Q4 vs. Q1, −3.85cm^2^, 95% CI: −7.01, −0.68, P=0.02; BMC at 6y: No significant associations; Area-adjusted BMC (aBMC) at 6y in all subjects: Q4 vs Q1, 4.96g, 95% CI: 1.27, 8.64, P<0.05; aBMC at 6y in subjects receiving vitamin D supplements at 14mo: Q4 vs. Q1, 2.73g, 95% CI: 0.62, 4.84, P=0.01
van den Hooven, 2015 (2); Prospective Cohort Study; n = 2,850; The Netherlands | Potatoes, Rice, and Vegetables Pattern (potatoes, pasta, rice, vegetables, meat, meat products, fish, shell-fish, oils, condiments, sauce): Adherence scores at 13mo, quartiles | BA, aBMC, BMD, BMC at 6y: No significant associations
van den Hooven, 2015 (2); Prospective Cohort Study; n = 2,850; The Netherlands | Refined Grains and Confectionery Pattern (refined grains, solid fats, confectionery, snack bar products, savory snacks, sugar-containing beverages): Adherence scores at 13mo, quartiles | BA, aBMC, BMD, BMC at 6y: No significant associations

### Included articles

1 Harvey, N C, Robinson, S M, Crozier, S R, Marriott, L D, Gale, C R, . Breast-feeding and adherence to infant feeding guidelines do not influence bone mass at age 4 years. Br J Nutr 2009;102(6):915–20.19338707
2 van den Hooven, E H, Heppe, D. H M, Kiefte-de J, J C, Medina G, C, Moll, H A, . Infant dietary patterns and bone mass in childhood: the Generation R Study. Osteoporosis International 2015;26:1595–604.25792489

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. This is the analytic framework for the systematic review conducted to examine the relationship between types and amounts of complementary foods and beverages and micronutrient status.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts all contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on types and/or amounts of CFB and bone health. For this systematic review, the target population considered was generally healthy infants fed humna milk, infant formula, or both, who had bone health measured through age 18 years. The interventions or exposures considered were the types and/or amounts of CFB consumed and their comparators were different types and/or amounts of CFB. Complementary feeding is defined as the process that starts when human milk or infant formula is complemented by other foods and beverages. The complementary feeding period typically continues to 24 months as the young child transitions fully to family foods.Complementary foods and beverages (CFB) are foods and beverages (liquids, semisolids, and solids) other than human milk or infant formula, provided to an infant or young child to provide nutrients and energy. The outcomes considered were Bone mass, including bone mineral density and bone mineral content, biomarkers of bone metabolism, and incidence and prevalence of osteoporosis, osteopenia, rickets, and/or fracture. The key confounders were education, socioeconomic status, sex, race and/or ethnicity, milk feeding practices (breast milk, infant formula, or both), birth size, and gestational age.

## SEARCH PLAN AND RESULTS

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review question: What is the relationship between types and/or amounts of complementary foods and beverages and bone health? The inclusion and exclusion criteria are a set of characteristics to determine which studies will be included or excluded in the systematic review.

Table 2 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | Randomized controlled trials | Cross-sectional studies
| Non-randomized controlled trials | Uncontrolled studies
| Prospective cohort studies | Pre/post studies without a control
| Retrospective cohort studies | Narrative reviews
| Case-control studies | Systematic reviews
| Pre/post studies with a control | Meta-analyses
Independent variable (intervention or exposure) | Types and/or amounts of complementary foods and beverages consumed (CFB) (i.e., foods and beverages (liquids, semisolids, and solids) other than human milk or infant formula provided to an infant or young child to provide nutrients and energy) | Consumption of fluid cow’s milk before 12 months of age
Comparator | Different types and/or amounts of CFB
Dependent variables (outcomes) | Bone mass, including bone mineral density and bone mineral content
| Biomarkers of bone metabolism
| Incidence and prevalence of osteoporosis, osteopenia, rickets, and/or fracture
Date range | January 1980 - July 2016
Language | Studies published in English | Studies published in languages other than English
Publication status | Studies published in peer-reviewed journals | Grey literature, including unpublished data, manuscripts, reports, abstracts, conference proceedings
Country^2,^ ^3,^ ^4^ | Studies conducted in Very High or High Human Development Countries | Studies conducted in Medium or Low Human Development Countries
Study participants | Human subjects | Hospitalized patients, not including birth and immediate post-partum hospitalization of healthy babies
| Males
| Females
Age of study participants | Age at intervention or exposure: Infants (0-12mo); Toddlers (12-24mo) | Age at intervention or exposure: Child (2-5 years (y)); Child (6-12y); Adolescents (13-18y); Adults (19y and older); Older adults (65 to 79y); Older adults (80+y)
| Age at outcome: Infants (0-12mo); Toddlers (12-24mo); Child (2-5 years (y)); Child (6-12y); Adolescents (13-18y) | Age at outcome: Adults (19y and older); Older adults (65 to 79y); Older adults (80+y)
Health status of study participants | Studies done in generally healthy populations | Studies that exclusively enroll subjects with a disease or with the health outcome of interest
| Studies done in populations where infants were full term (≥37wk gestational age) | Studies done in hospitalized or malnourished subjects
| Studies done in populations with elevated chronic disease risk, or that enroll some participants with a disease or with the health outcome of interest | Studies of exclusively pre-term babies (gestational age <37wk) or babies that are small for gestational age (<2500g)
| | Studies of subjects with infectious diseases (e.g. HIV/AIDS) (or with mothers diagnosed with an infectious disease)
Source of foods and beverages | Whole food sources | Human milk
| Fortified foods/beverages | Infant formulas (e.g., milk-based, soy, partially-hydrolyzed, extensive-hydrolyzed, amino acid-based)
| Enriched foods/beverages | Vitamin and mineral supplements (e.g., iron drops)

1 Risk of bias was assessed using the Nutrition Evidence Library Bias Assessment Tool. Available at nesr.usda.gov.

2 United Nations Development Programme. Human Development Report 2014: Reducing Vulnerabilities and Building Resilience. Available from: http://hdr.undp.org/en/content/human-development-report-2014.

3 Medium Development Countries were originally included, but due to concerns about generalizability to the U.S. of study participants (i.e., baseline health status) and CFB typically consumed, a decision was made to exclude “Medium” countries in October 2017.

4 When a country was not included in the Human Development Report 2014, country classification from the World Bank was used instead (The World Bank. Internet: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-bank-country-and-lending-groups (accessed March 27, 2018)

### Search terms and electronic databases used

#### PubMed, US National Library of Medicine (https://www.nlm.nih.gov/bsd/medline.html) (1966 to 19 July 2016)

Date(s) Searched: 7/19/2016

Search Terms:

Complementary OR supplementary OR wean* OR transition* OR introduc* OR “Infant Nutritional Physiological Phenomena”[Mesh:noexp] OR weaning[mesh] OR ((bottle*) NOT (milk OR formula))

AND (feeding* OR food OR beverage*[tiab] OR beverages[mh] OR eating OR diet[tiab] OR diet[mh] OR meal*[tiab] OR meals[mh] OR “Food and Beverages”[Mesh] OR diets[tiab] OR cereal*[tiab] OR “Edible Grain”[Mesh] OR bread*[tiab] OR whole grain* OR juice*[tiab] OR milk[tiab] OR “Milk”[Mesh] OR dairy[tiab] OR “Dairy Products”[Mesh] OR meat[tiab] OR cheese[tiab] OR yogurt[tiab] OR yoghurt*[tiab] OR fruit*[tiab] OR “Fruit”[Mesh] OR vegetable*[tiab] OR “Vegetables”[Mesh] OR egg*[tiab] OR “Eggs”[Mesh] OR nut[tiab] OR nuts[tiab] OR peas[tiab] OR beans[tiab] OR legume*[tiab] OR snack*[tiab] OR bread[mh] OR honey[mh] OR vegetable*[tiab] OR “Vegetables”[Mesh] OR egg*[tiab] OR “Eggs”[Mesh:noexp] OR “egg white”[mh] OR “egg yolk”[mh] OR snack*[tiab] OR candy[mh] OR “Fast Foods”[Mesh] OR meat[mh] OR molasses[mh] OR nuts[mh] OR “Raw Foods”[Mesh] OR seeds[mh])

OR “infant food”[mesh]

OR infant feed*

OR

(breast feeding[mh] OR breastfeeding[tiab] OR breast feeding*[tiab] OR breast-feeding*[tiab] OR breastfed[tiab] OR breast-fed[tiab] OR breast-feed OR breast-feeds)

OR

(Bottle feeding[mh] OR bottle feeding*[tiab]s OR bottle feeding OR bottle-feeding*[tiab] OR bottle-feedings OR bottle-fed[tiab] OR “bottle fed”[tiab])

NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic[sb])

OR ((Solid food*) OR solids));

AND

Growth[mh:noexp] OR “Child Development”[Mesh] OR “Growth Charts”[Mesh] OR “growth and development” [Subheading] OR “growth and development”[tiab] OR “Growth and Development”[Mesh:noexp] OR “Growth”[tiab] OR development*[tiab] OR “Child Development”[Mesh] OR child develop*[tiab] OR tooth[mh] OR tooth[tiab] OR teeth[tiab] OR movement[mh] OR “Overnutrition”[Mesh] OR under-nutrition[tiab] OR undernutrition[tiab] OR “developmental delay”[tiab] OR “Motor Skills”[Mesh] OR “Nonverbal Communication”[Mesh]

Standing[tiab] OR sitting[tiab] OR walking[tiab] OR crawling[tiab] OR “Motor Skills”[Mesh] OR Ages and Stages Questionnaire* OR ASQ[tiab]

OR Cognitive[tiab] OR cognition[mh] OR cognition OR learning OR “Learning Disorders”[Mesh] OR “Intellectual Disability”[Mesh] OR intelligence[tiab] OR intelligence[mh] OR “Achievement”[Mesh] OR “Aptitude”[Mesh] OR “Executive Function”[Mesh] OR memory OR inhibitory control*[tiab] OR “problem solving”[tiab] OR“Social-emotional development”[tiab] OR “Neurological development”[tiab] OR “mental development”[tiab] OR

“Motor development”[tiab] OR anxiety[tiab] OR anxiety[mh:noexp] OR “Anxiety, Separation”[Mesh] OR depression[tiab] OR depression[mh] OR “Depression, Postpartum”[Mesh] OR “Depressive Disorder”[Mesh] OR

“Visual Acuity”[Mesh] OR “Auditory Perception”[Mesh] OR “Psychological Tests”[Mesh]

OR

(“Bone Density”[Mesh] OR “bone density”[tiab] OR “Bone Development”[Mesh] OR “Bone Development”[tiab] OR “Fractures, Bone”[Mesh] OR “Bone Diseases”[Mesh] OR osteoporosis[tiab] OR (bone[tiab] AND fracture*[tiab]) OR “Rickets”[Mesh] OR ricket*[tiab] OR bone mineral*[tiab] OR “bone mass”[tiab] OR bone health*[tiab] OR “Bone Demineralization, Pathologic”[Mesh] OR bone demineral*[tiab])

OR

(“body size”[tiab] OR body size[mh] OR obesity[tiab] OR obese[tiab] OR overweight[mh] OR obesity[mh] OR overweight [tiab] OR adipos*[tiab] OR adiposity[mh] OR “body composition”[mh] OR body fat distribution[mh] OR “body fat”[tiab] OR “body weight”[tiab] OR body weight[mh] OR birth weight*[tiab] OR weight gain[mh] OR weight loss[mh] OR “body-weight”[tiab] OR “weight gain”[tiab] OR weight-gain[tiab] OR weight loss[tiab] OR weight-loss[tiab] OR “Body Weights and Measures”[mh] OR weight[ti] OR “Anthropometry”[Mesh:noexp] OR body mass index[mh] OR “body mass index”[tiab] OR BMI[tiab] OR “weight status”[tiab] OR “adipose tissue”[mh] OR “healthy weight”[tiab] OR waist circumference[mh] OR “body mass”[ti] OR “fat mass”[tiab] OR body weight changes[mh] OR “waist circumference”[tiab] OR ideal body weight[mh] OR waist-hip ratio[mh] OR Waist Hip*[tiab] OR body height*[tiab] OR Crown-Rump Length*[tiab] OR head circumference*[tiab] OR arm circumference*[tiab] OR thigh circumference* OR limb circumference* OR fat free mass*[tiab] OR skinfold[tiab] OR skin fold*[tiab])

AND

infant* OR baby OR babies OR toddler* OR newborn*[tiab] OR “Child, Preschool”[Mesh] OR preschool*[tiab] OR pre-school*[tiab] OR “early childhood”[tiab] OR “early years”[tiab] OR pre-k[tiab] OR pre-primary[tiab] OR under five*[ti] OR young child*[ti] OR “head start”[tiab] OR prekindergarten[tiab] OR pre-kindergarten[tiab] OR weanling*

OR limit to child, preschool

for child 0-18 all develop outcomes

for all; body wgt/comp/bone

NOT

nutritional status[mh] OR nutritional status*[tiab] OR Nutrition Status*[tiab] OR Iron[mh] OR iron[tiab] OR “Anemia”[Mesh] OR “Anemia”[tiab] OR iron deficien*[tiab] OR ferritin*[tiab] OR ferrous[tiab] OR “Transferrin”[Mesh] OR “Transferrin”[tiab] OR zinc OR “Vitamin D”[Mesh] OR “Vitamin D”[tiab] OR “Vitamin D Deficiency”[Mesh] OR “Vitamin B 12”[Mesh] OR “Vitamin B 12”[tiab] OR “Vitamin B12”[tiab] OR “Vitamin B 12 Deficiency”[Mesh] OR Cobamide*[tiab] OR Cobalamin*[tiab] OR Cyanocobalamin[tiab] OR Folate[tiab] OR “Folic Acid”[Mesh] OR folacin[tiab] OR vitamin b9*[tiab] OR Fatty acid*[tiab] OR “Fatty Acids”[Mesh:noexp] OR fatty acid*[tiab] OR “Fatty Acids, Unsaturated”[Mesh:noexp] OR Arachidonic acid*[tiab] OR linolenic acid*[tiab] OR linoleic acid*[tiab] OR Docosahexaenoic Acid*[tiab] OR Eicosapentaenoic Acid*[tiab] OR gamma-Linolenic Acid*[tiab] OR “Arachidonic Acids”[Mesh] OR “Fatty Acids, Essential”[Mesh] OR “Fatty Acids, Omega-3”[Mesh] OR “Fatty Acids, Omega-6”[Mesh] OR alpha-Linolenic Acid*[tiab] OR “Fatty Acids, Essential”[Mesh] OR “Linolenic Acids”[Mesh] OR “Trans Fatty Acids”[Mesh] OR “Fatty Acids, Monounsaturated”[Mesh]

for nonmedline[sb]: NOT animals by: NOT (sheep[ti] OR lamb[ti] OR lambs[ti] OR calving[ti] OR calves[ti] OR mice[ti] OR mouse[ti] OR pigs[ti] OR cows[ti] OR piglets[ti] OR cow[ti] OR piglet[ti] OR monkey[ti] OR rats[ti] OR rat[ti] OR animal*[ti])

#### Embase, Elsevier (https://www.elsevier.com/solutions/embase-biomedical-research/embase-coverage-and-content) (1947 to 1 August 2016)

Date(s) Searched: 8/1/16

Search Terms:

(Complementary OR supplementa* OR wean* OR transition* OR introduc* OR family) NEAR/3 (feed* OR food* OR beverage* OR eating OR diet)

OR

(Complementary OR transition* OR introduct* OR wean*) AND (food/exp OR ‘baby food’/exp OR ‘cereal’/exp OR ‘dairy product’/exp OR ‘egg’/exp OR ‘fruit’/exp OR ‘meat’/exp OR ‘sea food’/exp OR ‘milk’/exp OR fish/exp OR ‘poultry’/exp OR ‘beverage’/exp OR ‘vegetable’/exp OR nut/exp OR pea/exp OR meal/exp)

OR

(Complementary OR supplementa* OR wean* OR transition* OR introduc*) NEAR/5 (‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR beverage* OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR bread* OR yog*urt* OR cheese* OR juice* OR rice OR soup OR legume* OR snack* OR meal*) (for Embase)

OR ‘baby food’/de OR (solid NEAR/2 food*):ab,ti

AND

(infant*:ti,ab OR infant/exp) OR (baby OR babies OR toddler* OR newborn* OR nurser*):ti,ab OR ‘newborn’/exp OR ‘newborn care’/exp OR preschool*:ti,ab OR pre-school:ti,ab OR ‘preschool child’/exp OR ‘infancy’/exp OR “early childhood”:ti,ab OR “early years” OR pre-k:ti,ab OR ‘nursery’/exp OR ‘nursery school’/exp OR prekindergarten:ti,ab OR pre-kindergarten:ti,ab OR weanling*

AND ([in process]/lim OR [article]/lim OR [article in press]/lim) AND ([embase]/lim NOT [medline]/lim)

AND

Limit to humans:

AND

‘executive function’/exp OR ‘executive function’:ti,ab OR ‘learning’/exp OR ‘intelligence’/exp OR ‘mental development’/exp OR ‘mental development’:ti,ab OR intelligence:ti,ab OR cogniti*:ti,ab OR ‘cognition’/exp OR ‘cognition assessment’/exp OR aptitude:ti,ab OR ‘memory’/exp OR memory:ti,ab OR ‘anxiety’/exp OR ‘anxiety’:ti,ab OR ‘depression’/exp OR depressi*:ti,ab OR ‘visual acuity’/exp OR visual:ti OR ‘hearing’/exp OR hearing:ti,ab OR auditory:ti,ab OR ‘postnatal development’/exp OR ‘postnatal development’:ti,ab OR ‘overnutrition’/exp OR ‘overnutrition’:ti,ab OR undernutrition:ti,ab OR “developmental delay”:ti,ab OR ‘nonverbal communication’/exp

OR

(‘metabolic bone disease’/exp OR osteoporosis:ti,ab OR (bone NEAR/2 (disease* OR fracture* OR injur* OR health* OR density OR mineralize* OR demineraliz*)):ti,ab OR ricket*:ti,ab OR ‘bone injury’/exp OR ‘bone density’/exp)

AND

‘body size’/de OR ‘body size’:ti,ab OR ‘obesity’/exp OR overweight:ab,ti OR ‘macrosomia’/exp OR obese:ab,ti OR obesity:ab,ti OR ‘weight gain’:ab,ti OR adiposity:ab,ti OR adipose:ab,ti OR ‘body weight’/exp OR ‘body weight’:ti,ab OR ‘weight gain’/de OR ‘body composition’/exp OR ‘body composition’:ti,ab OR ‘body fat’:ab,ti OR ‘anthropometry’/de OR ‘body mass’/de OR bmi:ab,ti OR ‘body mass’:ab,ti OR weight:ab,ti OR (waist NEXT/1 hip NEXT/1 ratio*) OR ‘body fat’/de OR ‘adipose tissue’/exp OR skinfold OR ‘skin fold’:ti,ab OR ‘fat mass’:ti,ab OR ‘fat mass’/exp OR ‘anthropometric parameters’/exp OR circumference OR length OR height

OR

‘body growth’/exp ‘body growth’:ti,ab OR ‘growth rate and growth regulation’/exp OR ‘postnatal growth’/exp OR ‘human development’/exp OR ‘Bayley Scales of Infant Development’/exp OR ‘cognition assessment’/exp OR ‘mental function assessment’/de

#### Cochrane Central Register of Controlled Trials (https://handbook-5-1.cochrane.org/chapter_6/6_2_1_2_the_cochrane_central_register_of_controlled_trials.htm), John Wiley & Sons (searched 9 August 2016)

Date(s) Searched: 8/9/16

Search Terms:

(feed* OR food* OR beverage*OR diet* OR ‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR beans OR legume* OR nut OR cereal OR beverage* OR bread* OR seafood OR yog*urt* OR cheese OR juice OR snack OR yogurt OR yoghurt OR nut OR nuts OR honey OR meal OR meals) NEAR/3 (Complementary OR supplementa* OR wean* OR transition* OR introduct* OR family)

OR

[mh ^“Infant Nutritional Physiological Phenomena”] OR [mh weaning] OR ((bottle*) NOT (milk OR formula))

AND ([mh beverages] OR [mh eating] OR [mh diet] OR [mh meals] OR [mh “Food and Beverages”] OR [mh “Edible Grain”] OR [mh “Milk”] OR dairy[:ti,ab OR [mh “Dairy Products”] OR [mh “Fruit”] OR [mh “Vegetables”] OR [mh “Eggs”] OR [mh bread] OR [mh honey] OR [mh “Vegetables”] OR [mh ^“Eggs”] OR [mh “egg white”] OR [mh “egg yolk”] OR [mh candy] OR [mh “Fast Foods”] OR [mh meat] OR [mh molasses] OR [mh nuts] OR [mh “Raw Foods”] OR [mh seeds])

OR

((Infant* OR baby* OR babies) NEAR/2 food*):ti,ab OR [mh “infant food”]

AND

[mh ^Growth] OR [mh “Child Development”] OR [mh “Growth Charts”] OR “growth and development” OR [mh ^“Growth and Development”] OR [mh “Child Development”] OR (child NEAR/1 develop*):ti,ab OR [mh tooth] OR tooth:ti,ab OR teeth:ti,ab OR [mh movement] OR [mh “Overnutrition”] OR “under-nutrition:ti,ab OR undernutrition:ti,ab OR [mh “Motor Skills”] OR [mh “Nonverbal Communication”]

OR

‘body growth’:ti,ab OR ‘growth rate and growth regulation’ OR ‘postnatal growth’:ti,ab OR ‘human development’:ti,ab OR ‘Bayley Scales of Infant Development’

OR Standing:ti,ab OR sitting:ti,ab OR walking:ti,ab OR crawling:ti,ab OR “Ages and Stages Questionnaire” OR ASQ:ti,ab

OR [mh cognition] OR [mh learning] OR [mh “Learning Disorders”] OR [mh “Intellectual Disability”] OR intelligence:ti,ab OR [mh intelligence] OR [mh “Achievement”] OR [mh “Aptitude”] OR [mh “Executive Function”] OR (inhibitory NEAR/1 control*):ti,ab OR “problem solving”:ti,ab OR “Social-emotional development”:ti,ab OR “Neurological development”:ti,ab OR “mental development”:ti,ab OR “Motor development”ti,ab OR [mh ^anxiety] OR [mh “Anxiety, Separation”] OR [mh depression] OR [mh “Depression, Postpartum”] OR [mh “Depressive Disorder”] OR [mh “Visual Acuity”] OR [mh “Auditory Perception”] OR [mh “Psychological Tests”]

OR Stunt*:ti,ab OR wasting:ti,ab

OR

cogniti*:ti,ab OR aptitude:ti,ab OR memory:ti,ab OR [mh memory] OR ‘anxiety’:ti,ab OR depressi*:ti,ab OR visual:ti,ab OR vision:ti,ab OR hearing:ti,ab OR auditory:ti,ab OR ‘postnatal development’:ti,ab OR ‘overnutrition’:ti,ab OR “developmental delay”:ti,ab OR ‘nonverbal communication’

OR

[mh “Bone Density”] OR [mh “Bone Development”] OR [mh “Fractures, Bone”] OR [mh “Bone Diseases”] OR [mh “Rickets”] OR [mh “Bone Demineralization, Pathologic”] OR osteoporosis:ti,ab OR (bone NEAR/2 (disease* OR fracture* OR injur* OR health* OR density OR mineral* OR demineral* OR develop* OR mass)):ti,ab OR ricket*:ti,ab

OR

‘body size’:ti,ab OR overweight:ab,ti OR ‘macrosomia’:ti,ab OR obese:ab,ti OR obesity:ab,ti OR adipos*:ab,ti OR ‘body weight’:ti,ab OR ‘weight gain’:ti,ab OR ‘body composition’:ti,ab OR ‘body fat’:ab,ti OR ‘anthropometr*’:ti,ab OR bmi:ab,ti OR ‘body mass’:ab,ti OR (waist NEXT/1 hip NEXT/1 ratio*) OR ‘body fat’:ti,ab OR ‘adipose tissue’:ti,ab OR skinfold:ti,ab OR ‘skin fold’:ti,ab OR ‘fat mass’:ti,ab OR circumference:ti,ab OR length:ti,ab OR height:ti,ab

([mh “body size”] OR [mh overweight] OR [mh obesity] OR [mh adiposity] OR [mh “body composition”] OR [mh “body fat distribution”] OR [mh “body weight”] OR [mh “weight gain”] OR [mh “weight loss”] OR “weight gain”:ti,ab OR “weight loss”:ti,ab OR “weight-loss”:ti,ab OR [mh “Body Weights and Measures”] OR weight:ti OR [mh ^“Anthropometry”] OR [mh “body mass index”] OR “weight status”:ti,ab OR [mh “adipose tissue”] OR “healthy weight”:ti,ab OR [mh “waist circumference”] OR [mh “body weight changes”] OR [mh “ideal body weight”] OR [mh “waist-hip ratio”] OR “Waist Hip”:ti,ab OR “waist-hip”:ti,ab OR “Crown-Rump”:ti,ab OR “fat free mass”:ti,ab)

NOT (pubmed OR embase)

#### CINAHL Plus with Full Text, EBSCO (https://www.ebsco.com/products/research-databases/cinahl-plus-full-text) (Cumulative Index to Nursing and Allied Health Literature; 1937 to 22 August 2016)

Date(s) Searched: 8/22/2016

Search Terms:

(MH “Food and Beverages+”) OR (MH “Food”) OR (MH “Diet”) OR (MH “Eating”) OR (MH “Eating Behavior”) OR (MH “Taste”) OR (MH “Taste Buds”) OR (MH “Cereals”) OR (MH “Dairy Products”) OR (MH “Yogurt”) OR (MH “Cheese”) OR (MH “Milk”) OR (MH “Eggs”) OR (MH “Fruit”) OR (MH “Fruit Juices”) OR (MH “Meat”) OR (MH “Seafood”) OR (MH “Fish”) OR (MH “Poultry”) OR (MH “Vegetables”) OR (MH “Nuts”) OR (MH “Legumes”) OR (MH “Bread”) AND (Complementary OR supplementa* OR wean* OR transition* OR introduc*)

OR

(‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR beverage* OR bread* OR seafood OR yog*urt* OR cheese* OR juice*) N5 (Complementary OR supplementa* OR wean* OR transition* OR introduc* OR family)

OR (Infant* OR baby OR babies) N2 food*

NOT

(MH “Nutritional Status”) OR “nutritional status” OR (MH “Nutritional Requirements”) OR (MH “Vitamin D”) OR (MH “Vitamin D Deficiency”) OR (MH “Vitamin B12 Deficiency”) OR (MH “Anemia”) OR “anemia” OR (MH “Anemia, Iron Deficiency”) OR (MH “Iron”) OR (MH “Zinc”) OR (MH “Vitamin B12”) OR (MH “Vitamin B12 Deficiency”) OR (MH “Folic Acid”) OR (MH “Niacin”) OR (MH “Folic Acid Deficiency”) OR “folate” OR “folacin” OR cyanocobalamin* OR cobalamin* OR cobamamide* OR (MH “Fatty Acids”) OR “fatty acids” OR (MH “Fatty Acids, Omega-6”) OR (MH “Fatty Acids, Omega-3”) OR (MH “Fatty Acids, Unsaturated”) OR (MH “Trans Fatty Acids”) OR (MH “Fatty Acids, Monounsaturated”) OR (MH “Fatty Acids, Saturated”) OR (MH “Fatty Acids, Essential”) OR (MH “Arachidonic Acids”) OR (MH “Docosahexaenoic Acids”) OR (MH “Linolenic Acids”) OR (MH “Linoleic Acids”)

AND

osteoporosis OR (bone n2 (disease* OR fracture* OR injur* OR health* OR density OR mineralize* OR demineraliz*)) OR ricket* OR (MH “Osteoporosis”) OR (MH “Bone Density”) OR

(MH “Bone Diseases+”) OR (MH “Bone Diseases, Developmental+”) OR (MH “Rickets+”)

OR

(MH “Executive Function”) OR (MH “Learning+”) OR (MH “Intelligence+”) OR “intelligence” OR (MH “Intelligence Tests”) OR (MH “Cognition+”) OR “cognition” OR “mental development” OR (MH “Aptitude”) OR “aptitude” OR (MH “Aptitude Tests+”) OR (MH “Memory+”) OR “memory” OR (MH “Anxiety+”) OR “anxiety” OR (MH “Depression+”) OR “depression” OR (MH “Visual Acuity”) OR (MH “Visual Perception+”) OR (MH “Hearing+”) OR “auditory” OR “overnutrition” OR “undernutrition” OR (MH “Nonverbal Communication+”) OR “postnatal development” OR OR “developmental delay”

OR

(MH “Anthropometry+”) OR (MH “Body Weights and Measures+”) OR (MH “Body Weight+”) OR

(MH “Bone Development+”) OR (MH “Growth+”) OR (MH “Human Development+”) OR “bayley scales” OR “mental function” OR (MH “Body Size”) OR (MH “Obesity+”) OR “overweight” OR “macrosomia” OR (MH “Weight Gain+”) OR (MH “Waist-Hip Ratio”) OR (MH “Body Composition+”) OR (MH “Adipose Tissue+”) OR (MH “Abdominal Fat”) OR (MH “Fat Free Mass”) OR (MH “Body Mass Index”) OR (MH “Skinfold Thickness”) OR (MH “Head Circumference”) OR (MH “Arm Circumference”) OR (MH “Waist Circumference”) OR (MH “Growth and Development (Omaha)”) OR (MH “Body Height”) OR (MH “Crown-Rump Length”) OR (MH “Leg Length Inequality”) OR (MH “Mean Length of Utterance”)

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between complementary feeding and bone health. The literature search yielded 15,693 articles. During title screening, 13,272 articles were screened out. During abstract screening, 1,663 articles were screened out. During full-text screening, 642 articles were screened out. The systematic review on timing of introduction of CFB included three articles, and the systematic review on types and amounts of CFB consumed included two articles. The literature search was conducted for multiple systematic reviews that addressed complementary feeding and various health outcomes; the systematic reviews on developmental milestones and growth, size, and body composition are described in separate manuscripts.

This flow chart illustrates the literature search results for articles examining the relationship between complementary feeding and bone health. The results of an electronic database search were screened independently by two NESR analysts in a dual, step-wise manner by reviewing titles, abstracts, and full text articles to determine which articles met the criteria for inclusion. A manual search was done to ascertain articles not identified through the electronic database search. The systematic review on timing of introduction of CFB included three articles, and the systematic review on types and amounts of CFB consumed included two articles. The literature search was conducted for multiple systematic reviews that addressed complementary feeding and various health outcomes; the systematic reviews on developmental milestones and growth, size, and body composition are described in separate reports.

### Excluded articles

The table below lists the excluded articles with at least one reason for exclusion, but may not reflect all possible reasons.

Table 3 Excluded articles

| Citation | Rationale
1 | Complementary feeding in the WHO Multicentre Growth Reference Study. Acta Paediatr Suppl.2006;450:27-37. | DV
2 | Weaning and the weaning diet. Report of the Working Group on the Weaning Diet of the Committee on Medical Aspects of Food Policy. Rep Health Soc Subj (Lond).1994;45:1-113. | Design
3 | Aarts, C.,Kylberg, E.,Hofvander, Y.,Gebre-Medhin, M. Growth under privileged conditions of healthy Swedish infants exclusively breastfed from birth to 4-6 months: a longitudinal prospective study based on daily records of feeding. Acta Paediatr.2003;92:145-51. | IV
4 | Abarin, T.,Yan Wu, Y.,Warrington, N.,Lye, S.,Pennell, C.,Briollais, L. The impact of breastfeeding on FTO-related BMI growth trajectories: an application to the Raine pregnancy cohort study. Int J Epidemiol.2012;41:1650-60. | IV
5 | Abou Samra, H.,Stevens, D.,Binkley, T.,Specker, B. Determinants of bone mass and size in 7-year-old former term, late-preterm, and preterm boys. Osteoporos Int.2009;20:1903-10. | Design, IV
6 | Aboud, F. E.,Akhter, S. A cluster-randomized evaluation of a responsive stimulation and feeding intervention in bangladesh. Pediatrics.2011;127:e1191-7. | IV
7 | Aboud, F. E.,Shafique, S.,Akhter, S. A responsive feeding intervention increases children’s self-feeding and maternal responsiveness but not weight gain. J Nutr.2009;139:1738-43. | IV
8 | Adu-Afarwuah, S.,Lartey, A.,Brown, K. H.,Zlotkin, S.,Briend, A.,Dewey, K. G. Randomized comparison of 3 types of micronutrient supplements for home fortification of complementary foods in Ghana: effects on growth and motor development. Am J Clin Nutr.2007;86:412-20. | IV
9 | Agarwal, K. N.,Agarwal, D. K.,Gupta, A.,Bansal, A. K. Relationship of exclusive breast feeding for 6 mo to linear growth up to 18 mo of age. Indian J Pediatr.2013;80:11-5. | Country
10 | Aggarwal, A.,Arora, S.,Patwari, A. K. Breastfeeding among urban women of low-socioeconomic status: factors influencing introduction of supplemental feeds before four months of age. Indian Pediatr.1998;35:269-73. | Design, IV, DV
11 | Agostoni, C.,Fiocchi, A.,Riva, E.,Terracciano, L.,Sarratud, T.,Martelli, A.,Lodi, F.,D’Auria, E.,Zuccotti, G.,Giovannini, M. Growth of infants with IgE-mediated cow’s milk allergy fed different formulas in the complementary feeding period. Pediatr Allergy Immunol.2007;18:599-606. | IV
12 | Agostoni, C.,Grandi, F.,Gianni, M. L.,Silano, M.,Torcoletti, M.,Giovannini, M.,Riva, E. Growth patterns of breast fed and formula fed infants in the first 12 months of life: an Italian study. Arch Dis Child.1999;81:395-9. | IV
13 | Agostoni, C.,Grandi, F.,Scaglioni, S.,Gianni, M. L.,Torcoletti, M.,Radaelli, G.,Fiocchi, A.,Riva, E. Growth pattern of breastfed and nonbreastfed infants with atopic dermatitis in the first year of life. Pediatrics.2000;106:E73. | IV
14 | Agostoni,C.,Marangoni,F.,Lammardo,A. M.,Giovannini,M.,Riva,E.,Galli,C. Breastfeeding duration, milk fat composition and developmental indices at 1 year of life among breastfed infants. Prostaglandins Leukot Essent Fatty Acids.2001;64:105-9. | IV
15 | Agostoni,C.,Zuccotti,G. V.,Radaelli,G.,Besana,R.,Podesta,A.,Sterpa,A.,Rottoli,A.,Riva,E.,Giovannini,M. Docosahexaenoic acid supplementation and time at achievement of gross motor milestones in healthy infants: a randomized, prospective, double-blind, placebo-controlled trial. Am J Clin Nutr.2009;89:64-70. | IV
16 | Allen, L.,Shrimpton, R. The International Research on Infant Supplementation study: implications for programs and further research. J Nutr.2005;135:666s-669s. | Design
17 | Alm,B.,Aberg,N.,Erdes,L.,Mollborg,P.,Pettersson,R.,Norvenius,S. G.,Goksor,E.,Wennergren,G. Early introduction of fish decreases the risk of eczema in infants. Arch Dis Child.2009;94:11-5. | DV
18 | Almqvist,C.,Garden,F.,Xuan,W.,Mihrshahi,S.,Leeder,S. R.,Oddy,W.,Webb,K.,Marks,G. B. Omega-3 and omega-6 fatty acid exposure from early life does not affect atopy and asthma at age 5 years. J Allergy Clin Immunol.2007;119:1438-44. | IV, DV
19 | Alvarez-Uria, G.,Midde, M.,Pakam, R.,Bachu, L.,Naik, P. K. Effect of Formula Feeding and Breastfeeding on Child Growth, Infant Mortality, and HIV Transmission in Children Born to HIV-Infected Pregnant Women Who Received Triple Antiretroviral Therapy in a Resource-Limited Setting: Data from an HIV Cohort Study in India. ISRN Pediatr.2012;2012:763591. | Health status
20 | Andersen, L. B.,Molgaard, C.,Michaelsen, K. F.,Carlsen, E. M.,Bro, R.,Pipper, C. B. Indicators of dietary patterns in Danish infants at 9 months of age. Food Nutr Res.2015;59:27665. | Design
21 | Andersen,A. D.,Michaelsen,K. F.,Hellgren,L. I.,Trolle,E.,Lauritzen,L. A randomized controlled intervention with fish oil versus sunflower oil from 9 to 18 months of age: exploring changes in growth and skinfold thicknesses. Pediatr Res.2011;70:368-74. | IV
22 | Andersen,L. B.,Pipper,C. B.,Trolle,E.,Bro,R.,Larnkjaer,A.,Carlsen,E. M.,Molgaard,C.,Michaelsen,K. F. Maternal obesity and offspring dietary patterns at 9 months of age. Eur J Clin Nutr.2015;69:668-75. | DV
23 | Anderson, G. H.,Morson-Pasut, L. A.,Bryan, H.,Cleghorn, G.,Tanaka, P.,Yeung, D.,Zimmerman, B. Age of introduction of cow’s milk to infants. J Pediatr Gastroenterol Nutr.1985;4:692-8. | Design
24 | Anderson, V. P.,Cornwall, J.,Jack, S.,Gibson, R. S. Intakes from non-breastmilk foods for stunted toddlers living in poor urban villages of Phnom Penh, Cambodia, are inadequate. Matern Child Nutr.2008;4:146-59. | Design, Health status
25 | Andres, A.,Casey, P. H.,Cleves, M. A.,Badger, T. M. Body fat and bone mineral content of infants fed breast milk, cow’s milk formula, or soy formula during the first year of life. J Pediatr.2013;163:49-54. | IV
26 | Andres, A.,Cleves, M. A.,Bellando, J. B.,Pivik, R. T.,Casey, P. H.,Badger, T. M. Developmental status of 1-year-old infants fed breast milk, cow’s milk formula, or soy formula. Pediatrics.2012;129:1134-40. | IV
27 | Andrissi, L.,Mottini, G.,Sebastiani, V.,Boldrini, L.,Giuliani, A. Dietary habits and growth: an urban/rural comparison in the Andean region of Apurimac, Peru. Ann Ist Super Sanita.2013;49:340-6. | IV
28 | Anfield,L. Nutrition in the first year. Midwife Health Visit Community Nurse.1985;21:161-4. | Design
29 | Anzman-Frasca, S.,Liu, S.,Gates, K. M.,Paul, I. M.,Rovine, M. J.,Birch, L. L. Infants’ Transitions out of a Fussing/Crying State Are Modifiable and Are Related to Weight Status. Infancy.2013;18:662-686. | IV
30 | Armstrong, J.,Reilly, J. J. Breastfeeding and lowering the risk of childhood obesity. Lancet.2002;359:2003-4. | IV
31 | Arsenault,J. E.,Havel,P. J.,Lopez de Romana,D.,Penny,M. E.,Van Loan,M. D.,Brown,K. H. Longitudinal measures of circulating leptin and ghrelin concentrations are associated with the growth of young Peruvian children but are not affected by zinc supplementation. Am J Clin Nutr.2007;86:1111-9. | Health status
32 | Arvas, A.,Elgormus, Y.,Gur, E.,Alikasifoglu, M.,Celebi, A. Iron status in breast-fed full-term infants. Turk J Pediatr.2000;42:22-6. | IV
33 | Asha Bai, P. V.,Leela, M.,Subramaniam, V. R. Adequacy of breast milk for optimal growth of infants. Trop Geogr Med.1980;32:158-62. | IV
34 | Assuncao, M. L.,Ferreira, H. S.,Coutinho, S. B.,Santos, L. M.,Horta, B. L. Protective effect of breastfeeding against overweight can be detected as early as the second year of life: a study of children from one of the most socially-deprived areas of Brazil. J Health Popul Nutr.2015;33:85-91. | Design, Health status, IV
35 | Atladottir, H.,Thorsdottir, I. Energy intake and growth of infants in Iceland-a population with high frequency of breast-feeding and high birth weight. Eur J Clin Nutr.2000;54:695-701. | IV
36 | Auestad,N. Infant nutrition--brain development--disease in later life. An introduction. Dev Neurosci.2000;22:472-3. | Design
37 | Augusto,R. A.,Souza,J. M. Effectiveness of a supplementary feeding program in child weight gain. Rev Saude Publica.2010;44:793-801. | Design, IV
38 | Axelsson,I. E.,Jakobsson,I.,Raiha,N. C. Formula with reduced protein content: effects on growth and protein metabolism during weaning. Pediatr Res.1988;24:297-301. | IV
39 | Azad, M. B.,Konya, T.,Maughan, H.,Guttman, D. S.,Field, C. J.,Chari, R. S.,Sears, M. R.,Becker, A. B.,Scott, J. A.,Kozyrskyj, A. L. Gut microbiota of healthy Canadian infants: profiles by mode of delivery and infant diet at 4 months. Cmaj.2013;185:385-94. | DV
40 | Badger, T. Effects of soy infant formula on growth and development in the first year of life. Food Nutr Bull.2013;34:252-3. | Design, IV
41 | Bahamondes L,Bahamondes MV,Modesto W,Tilley IB,Magalhaes A,Pinto e Silva JL,Amaral E, Jr. Mishell DR. Effect of hormonal contraceptives during breastfeeding on infant’s milk ingestion and growth. Fertil Steril.2013;100:445-50. | IV
42 | Bai, K. I.,Sastry, V. N.,Reddy, C. C. A comparative study of feeding pattern of infants in rural and urban areas. Indian J Pediatr.1981;48:277-80. | Design, IV
43 | Balaban, G.,Motta, M. E.,Silva, G. A. Early weaning and other potential risk factors for overweight among preschool children. Clinics (Sao Paulo).2010;65:181-7. | IV, Age
44 | Balogun,T. A.,Lombard,M. J.,McLachlan,M. The nutrient intake of children aged 12-36 months living in two communities in the Breede Valley, Western Cape province, South Africa. South African Family Practice.2015;57:1-7 7p. | Design
45 | Baranowski, T.,Bryan, G. T.,Harrison, J. A.,Rassin, D. K.,Greaves, K. A.,Baranowski, J. H. Height, infant-feeding practices and cardiovascular functioning among 3 or 4 year old children in three ethnic groups. J Clin Epidemiol.1992;45:513-8. | DV
46 | Bartok, C. J.,Schaefer, E. W.,Beiler, J. S.,Paul, I. M. Role of body mass index and gestational weight gain in breastfeeding outcomes. Breastfeed Med.2012;7:448-56. | IV, DV
47 | Beal, V. A. Nutrition and growth-patterns of young children. ASDC J Dent Child.1983;50:139-41. | Design
48 | Begum, H. A.,Mascie-Taylor, C.,Nahar, S. The impact of food supplementation on infant weight gain in rural Bangladesh; an assessment of the Bangladesh Integrated Nutritional Program (BINP). Public Health Nutr.2007;10:49-54. | IV
49 | Beinner,M. A.,Velasquez-Melendez,G.,Pessoa,M. C.,Greiner,T. Iron-fortified rice is as efficacious as supplemental iron drops in infants and young children. J Nutr.2010;140:49-53. | IV, DV
50 | Ben,X. M.,Zhou,X. Y.,Zhao,W. H.,Yu,W. L.,Pan,W.,Zhang,W. L.,Wu,S. M.,Van Beusekom,C. M.,Schaafsma,A. Growth and development of term infants fed with milk with long-chain polyunsaturated fatty acid supplementation. Chin Med J (Engl).2004;117:1268-70. | IV
51 | Bennett,W. E.,Jr.,Hendrix,K. S.,Thompson-Fleming,R. T.,Downs,S. M.,Carroll,A. E. Early cow’s milk introduction is associated with failed personal-social milestones after 1 year of age. Eur J Pediatr.2014;173:887-92. | IV
52 | Bergmann, K. E.,Bergmann, R. L.,Von Kries, R.,Bohm, O.,Richter, R.,Dudenhausen, J. W.,Wahn, U. Early determinants of childhood overweight and adiposity in a birth cohort study: role of breast-feeding. Int J Obes Relat Metab Disord.2003;27:162-72. | IV
53 | Bernal, M. J.,Periago, M. J.,Martinez, R.,Ortuno, I.,Sanchez-Solis, M.,Ros, G.,Romero, F.,Abellan, P. Effects of infant cereals with different carbohydrate profiles on colonic function--randomised and double-blind clinical trial in infants aged between 6 and 12 months--pilot study. Eur J Pediatr.2013;172:1535-42. | IV
54 | Berni Canani R,Nocerino R,Terrin G,Frediani T,Lucarelli S,Cosenza L,Passariello A,Leone L,Granata V,Di Costanzo M,Pezzella V,Troncone R. Formula selection for management of children with cow’s milk allergy influences the rate of acquisition of tolerance: a prospective multicenter study. J Pediatr.2013;163:771-7.e1. | IV, DV
55 | Betoko, A.,Charles, M. A.,Hankard, R.,Forhan, A.,Bonet, M.,Regnault, N.,Botton, J.,Saurel-Cubizolles, M. J.,de Lauzon-Guillain, B. Determinants of infant formula use and relation with growth in the first 4 months. Matern Child Nutr.2014;10:267-79. | IV
56 | Betoko, A.,Charles, M. A.,Hankard, R.,Forhan, A.,Bonet, M.,Saurel-Cubizolles, M. J.,Heude, B.,de Lauzon-Guillain, B. Infant feeding patterns over the first year of life: influence of family characteristics. Eur J Clin Nutr.2013;67:631-7. | DV
57 | Bhandari, N.,Bahl, R.,Nayyar, B.,Khokhar, P.,Rohde, J. E.,Bhan, M. K. Food supplementation with encouragement to feed it to infants from 4 to 12 months of age has a small impact on weight gain. J Nutr.2001;131:1946-51. | Country
58 | Bhandari, N.,Mazumder, S.,Bahl, R.,Martines, J.,Black, R. E.,Bhan, M. K. An educational intervention to promote appropriate complementary feeding practices and physical growth in infants and young children in rural Haryana, India. J Nutr.2004;134:2342-8. | IV
59 | Bhatia, B. D.,Banerjee, D.,Agarwal, D. K.,Agarwal, K. N. Exterogestate growth: relationship with maternal body size and dietary intakes. Indian J Pediatr.1983;50:241-6. | Health status, IV
60 | Bindon, J. R.,Cabrera, C. Infant feeding patterns and growth of infants in American Samoa during the first year of life. Hum Biol.1988;60:81-92. | Design, IV, DV
61 | Bindon, J. R. The body build and composition of Samoan children: relationships to infant feeding patterns and infant weight-for-length status. Am J Phys Anthropol.1984;63:379-88. | IV
62 | Bindon, J. R. The influence of infant feeding patterns on growth of children in American Samoa. Med Anthropol.1985;9:183-95. | Country
63 | Birch,E. E.,Garfield,S.,Castaneda,Y.,Hughbanks-Wheaton,D.,Uauy,R.,Hoffman,D. Visual acuity and cognitive outcomes at 4 years of age in a double-blind, randomized trial of long-chain polyunsaturated fatty acid-supplemented infant formula. Early Hum Dev.2007;83:279-84. | IV
64 | Bisimwa, G.,Owino, V. O.,Bahwere, P.,Dramaix, M.,Donnen, P.,Dibari, F.,Collins, S. Randomized controlled trial of the effectiveness of a soybean-maize-sorghum-based ready-to-use complementary food paste on infant growth in South Kivu, Democratic Republic of Congo. Am J Clin Nutr.2012;95:1157-64. | IV
65 | Bjorke-Monsen, A. L. Is exclusive breastfeeding ensuring an optimal micronutrient status and psychomotor development in infants?. Clin Biochem.2014;47:714. | Design
66 | Block,S. L. Delayed introduction of solid foods to infants: not so fast!. Pediatr Ann.2013;42:143-7. | Design
67 | Bogen, D. L.,Hanusa, B. H.,Whitaker, R. C. The effect of breast-feeding with and without formula use on the risk of obesity at 4 years of age. Obes Res.2004;12:1527-35. | IV
68 | Bonuck, K.,Avraham, S. B.,Lo, Y.,Kahn, R.,Hyden, C. Bottle-weaning intervention and toddler overweight. J Pediatr.2014;164:306-12.e1-2. | IV
69 | Borschel, M. W.,Baggs, G. E.,Barrett-Reis, B. Growth of healthy term infants fed ready-to-feed and powdered forms of an extensively hydrolyzed casein-based infant formula: a randomized, blinded, controlled trial. Clin Pediatr (Phila).2014;53:585-92. | IV
70 | Boulton J. Nutrition in childhood and its relationships to early somatic growth, body fat, blood pressure, and physical fitness. Acta Paediatr Scand Suppl.1981;284:1-85. | Design, DV
71 | Brakohiapa, L. A.,Yartey, J.,Bille, A.,Harrison, E.,Quansah, E.,Armar, M. A.,Kishi, K.,Yamamoto, S. Does prolonged breastfeeding adversely affect a child’s nutritional status?. Lancet.1988;2:416-8. | IV, DV
72 | Brazionis, L.,Golley, R. K.,Mittinty, M. N.,Smithers, L. G.,Emmett, P.,Northstone, K.,Lynch, J. W. Diet spanning infancy and toddlerhood is associated with child blood pressure at age 7.5 y. Am J Clin Nutr.2013;97:1375-86. | DV
73 | Breij, L. M.,Mulder, M. T.,van Vark-van der Zee, L. C.,Hokken-Koelega, A. C. Appetite-regulating hormones in early life and relationships with type of feeding and body composition in healthy term infants. Eur J Nutr.2016. | IV
74 | Brekke, H. K.,van Odijk, J.,Ludvigsson, J. Predictors and dietary consequences of frequent intake of high-sugar, low-nutrient foods in 1-year-old children participating in the ABIS study. Br J Nutr.2007;97:176-81. | DV
75 | Brew,B. K.,Toelle,B. G.,Webb,K. L.,Almqvist,C.,Marks,G. B. Omega-3 supplementation during the first 5 years of life and later academic performance: a randomised controlled trial. Eur J Clin Nutr.2015;69:419-24. | IV
76 | Briend,A.,Bari,A. Breastfeeding improves survival, but not nutritional status, of 12-35 months old children in rural Bangladesh. Eur J Clin Nutr.1989;43:603-8. | Health status, IV
77 | Briend,A.,Darmon,N. Determining limiting nutrients by linear programming: A new approach to predict insufficient intakes from complementary foods. Pediatrics.2000;106:1288-9. | Design
78 | Brito,A.,Olivares,M.,Pizarro,T.,Rodriguez,L.,Hertrampf,E. Chilean complementary feeding program reduces anemia and improves iron status in children aged 11 to 18 months. Food Nutr Bull.2013;34:378-85. | Design
79 | Brown A,Lee MD. Early influences on child satiety-responsiveness: the role of weaning style. Pediatr Obes.2015;10:57-66. | IV
80 | Brown, A.,Lee, M. Breastfeeding during the first year promotes satiety responsiveness in children aged 18-24 months. Pediatr Obes.2012;7:382-90. | IV
81 | Brown,K. H.,Lopez de Romana,D.,Arsenault,J. E.,Peerson,J. M.,Penny,M. E. Comparison of the effects of zinc delivered in a fortified food or a liquid supplement on the growth, morbidity, and plasma zinc concentrations of young Peruvian children. Am J Clin Nutr.2007;85:538-47. | IV
82 | Brown,L. V.,Zeitlin,M. F.,Peterson,K. E.,Chowdhury,A. M.,Rogers,B. L.,Weld,L. H.,Gershoff,S. N. Evaluation of the impact of weaning food messages on infant feeding practices and child growth in rural Bangladesh. Am J Clin Nutr.1992;56:994-1003. | IV
83 | Brulotte, J.,Bukutu, C.,Vohra, S. Complementary, holistic, and integrative medicine: fish oils and neurodevelopmental disorders. Pediatr Rev.2009;30:e29-33. | Design
84 | Bulk-Bunschoten, A. M.,van Bodegom, S.,Reerink, J. D.,de Jong, P. C.,de Groot, C. J. Weight and weight gain at 4 months (The Netherlands 1998): influences of nutritional practices, socio-economic and ethnic factors. Paediatr Perinat Epidemiol.2002;16:361-9. | IV
85 | Burnham, L.,Matlak, S.,Makrigiorgos, G.,Braun, N.,Knapp, B. P.,Merewood, A. Breastfeeding and coffee consumption in children younger than 2 years in Boston, Massachusetts, USA. J Hum Lact.2015;31:267-72. | DV
86 | Caleyachetty A,Krishnaveni GV,Veena SR,Hill J,Karat SC,Fall CH,Wills AK. Breastfeeding duration, age of starting solids and high BMI risk and adiposity in Indian children. Matern Child Nutr.2013;9:199-216. | Design, Country
87 | Calvo,E. B.,Galindo,A. C.,Aspres,N. B. Iron status in exclusively breast-fed infants. Pediatrics.1992;90:375-9. | IV, DV
88 | Calvo,E.,Hertrampf,E.,Pablo,S.,Amar,M.,Stekel,A. Haemoglobin-fortified cereal: an alternative weaning food with high iron bioavailability. European journal of clinical nutrition.1989;43:237-43. | Design, DV
89 | Cameron, S. L.,Heath, A. L.,Gray, A. R.,Churcher, B.,Davies, R. S.,Newlands, A.,Galland, B. C.,Sayers, R. M.,Lawrence, J. A.,Taylor, B. J.,Taylor, R. W. Lactation Consultant Support from Late Pregnancy with an Educational Intervention at 4 Months of Age Delays the Introduction of Complementary Foods in a Randomized Controlled Trial. J Nutr.2015;145:1481-90. | DV
90 | Capozzi,L.,Russo,R.,Bertocco,F.,Ferrara,D.,Ferrara,M. Diet and iron deficiency in the first year of life: a retrospective study. Hematology.2010;15:410-3. | DV
91 | Capozzi,L.,Russo,R.,Bertocco,F.,Ferrara,D.,Ferrara,M. Effect on haematological and anthropometric parameters of iron supplementation in the first 2 years of life. Risks and benefits. Hematology.2011;16:261-4. | IV
92 | Carruth,B. R.,Nevling,W.,Skinner,J. D. Developmental and food profiles of infants born to adolescent and adult mothers. J Adolesc Health.1997;20:434-41. | IV, DV, Age
93 | Casiday, R. E.,Wright, C. M.,Panter-Brick, C.,Parkinson, K. N. Do early infant feeding patterns relate to breast-feeding continuation and weight gain? Data from a longitudinal cohort study. Eur J Clin Nutr.2004;58:1290-6. | IV
94 | Castillo-Duran,C.,Perales,C. G.,Hertrampf,E. D.,Marin,V. B.,Rivera,F. A.,Icaza,G. Effect of zinc supplementation on development and growth of Chilean infants. J Pediatr.2001;138:229-35. | IV
95 | Chaimay, B.,Ruagdaraganon, N.,Thinkhamrop, B.,Thinkhamrop, J. Association between infant feeding practices and first meaningful words at first year of life: a prospective cohort study of Thai children. Asia Pac J Public Health.2015;27:Np1071-84. | IV
96 | Chan,G. M.,Roberts,C. C.,Folland,D.,Jackson,R. Growth and bone mineralization of normal breast-fed infants and the effects of lactation on maternal bone mineral status. Am J Clin Nutr.1982;36:438-43. | IV
97 | Chang, S. Y.,He, W.,Chen, C. M. Complementary feeding and growth of infant and young child in China. Biomed Environ Sci.2008;21:264-8. | Design
98 | Chatterjee, M. K. Feeding pattern practised by the mothers attending an under five clinic. Indian J Public Health.1987;31:268-9. | Design
99 | Chavez A,Martinez C,Schlaepfer L. Health effects of supplementary feeding programs. Prog Clin Biol Res.1981;67:129-39. | Design
100 | Chawla, P.,Puri, R.,Pershad, D. Impact of pre-school supplementary feeding on mental abilities. Indian Pediatr.1983;20:513-6. | Age
101 | Chawla, P.,Puri, R. Impact of pre-school supplementary feeding programme on anthropometry. Indian Pediatr.1983;20:363-7. | Age
102 | Cheng, T. S.,Loy, S. L.,Cheung, Y. B.,Chan, J. K.,Pang, W. W.,Godfrey, K. M.,Gluckman, P. D.,Kwek, K.,Saw, S. M.,Chong, Y. S.,Lee, Y. S.,Lek, N.,Yap, F. Sexually dimorphic response to feeding mode in the growth of infants. Am J Clin Nutr.2016;103:398-405. | IV
103 | Chirmulay, D.,Nisal, R. Nutritional status of tribal underfive children in Ahmadnagar District, Maharashtra in relation to weaning/feeding practices. Indian Pediatr.1993;30:215-22. | Design
104 | Chitra, P. Development of banana-based weaning food mixes for infants and its nutritional quality evaluation. Rev Environ Health.2015;30:125-30. | IV
105 | Chivers, P.,Hands, B.,Parker, H.,Bulsara, M.,Beilin, L. J.,Kendall, G. E.,Oddy, W. H. Body mass index, adiposity rebound and early feeding in a longitudinal cohort (Raine Study). Int J Obes (Lond).2010;34:1169-76. | IV
106 | Cho, H. N.,Hong, S.,Lee, S. H.,Yum, H. Y. Nutritional status according to sensitized food allergens in children with atopic dermatitis. Allergy, Asthma and Immunology Research.2010;3:53-57. | Design, IV, DV
107 | Chorell,E.,Karlsson Videhult,F.,Hernell,O.,Antti,H.,West,C. E. Impact of probiotic feeding during weaning on the serum lipid profile and plasma metabolome in infants. Br J Nutr.2013;110:116-26. | IV
108 | Choudhury, N.,Bromage, S.,Alam, M. A.,Ahmed, A. M.,Islam, M. M.,Hossain, M. I.,Mahfuz, M.,Mondal, D.,Haque, M. R.,Ahmed, T. Intervention study shows suboptimal growth among children receiving a food supplement for five months in a slum in Bangladesh. Acta Paediatr.2016. | Health status, IV
109 | Christoffel, K. A pediatric perspective on vegetarian nutrition. Clin Pediatr (Phila).1981;20:632-43. | Design
110 | Christopher, G. C. First food: the essential role of breastfeeding. Breastfeed Med.2009;4 Suppl 1:S9-s10. | Design
111 | Chuang, C. H.,Yang, S. H.,Chang, P. J.,Chen, P. C.,Chen, Y. C. Dietary supplement intake by 6-month-old Taiwanese infants. J Pediatr Gastroenterol Nutr.2012;54:71-6. | DV
112 | Closa-Monasterolo, R.,Gispert-Llaurado, M.,Luque, V.,Ferre, N.,Rubio-Torrents, C.,Zaragoza-Jordana, M.,Escribano, J. Safety and efficacy of inulin and oligofructose supplementation in infant formula: results from a randomized clinical trial. Clin Nutr.2013;32:918-27. | IV
113 | Cloutier, M. M.,Wiley, J.,Wang, Z.,Grant, A.,Gorin, A. A. The Early Childhood Obesity Prevention Program (ECHO): an ecologically-based intervention delivered by home visitors for newborns and their mothers. BMC Public Health.2015;15:584. | Design
114 | Cockburn,F. Neonatal brain and dietary lipids. Arch Dis Child Fetal Neonatal Ed.1994;70:F1-2. | Design
115 | Cohen RJ,Brown KH,Canahuati J,Rivera LL,Dewey KG. Effects of age of introduction of complementary foods on infant breast milk intake, total energy intake, and growth: a randomised intervention study in Honduras. Lancet.1994;344:288-93. | Country
116 | Cohen, R. J.,Brown, K. H.,Canahuati, J.,Rivera, L. L.,Dewey, K. G. Determinants of growth from birth to 12 months among breast-fed Honduran infants in relation to age of introduction of complementary foods. Pediatrics.1995;96:504-10. | IV
117 | Coleman,B. L. Early introduction of non-formula cow’s milk to southern Ontario infants. Can J Public Health.2006;97:187-90. | IV, DV
118 | Colombo,J.,Carlson,S. E.,Cheatham,C. L.,Shaddy,D. J.,Kerling,E. H.,Thodosoff,J. M.,Gustafson,K. M.,Brez,C. Long-term effects of LCPUFA supplementation on childhood cognitive outcomes. Am J Clin Nutr.2013;98:403-12. | IV
119 | Coppi, S.,Iacoponi, F.,Fommei, C.,Strambi, M. Growth trend during the first six months of life in male infants with different type of feeding. Minerva Pediatr.2013;65:51-9. | IV
120 | Costom, B. H.,Shore, D. Effect of a comprehensive nutritional program on the growth and ponderosity of infants. Clin Pediatr (Phila).1983;22:105-11. | Design
121 | Courage, M. L.,McCloy, U. R.,Herzberg, G. R.,Andrews, W. L.,Simmons, B. S.,McDonald, A. C.,Mercer, C. N.,Friel, J. K. Visual acuity development and fatty acid composition of erythrocytes in full-term infants fed breast milk, commercial formula, or evaporated milk. J Dev Behav Pediatr.1998;19:9-17. | IV
122 | Cusack, R. Dietary management of obese children and adolescents. Pediatr Ann.1984;13:455, 458-9, 462-4. | Design
123 | Dagan, R.,Sofer, S.,Klish, W. J.,Hundt, G.,Saltz-Rennert, H.,Moses, S. W. Infant feeding practices among Bedouins in transition from seminomadic to settlement conditions in the Negev area of Israel. Isr J Med Sci.1984;20:1029-34. | Design, DV
124 | Dagnelie,P. C.,van Staveren,W. A.,Hautvast,J. G. Stunting and nutrient deficiencies in children on alternative diets. Acta Paediatr Scand Suppl.1991;374:111-8. | DV
125 | Dagnelie,P. C.,van Staveren,W. A.,Vergote,F. J.,Dingjan,P. G.,van den Berg,H.,Hautvast,J. G. Increased risk of vitamin B-12 and iron deficiency in infants on macrobiotic diets. Am J Clin Nutr.1989;50:818-24. | Design, DV
126 | Dagnelie,P. C.,van Staveren,W. A.,Verschuren,S. A.,Hautvast,J. G. Nutritional status of infants aged 4 to 18 months on macrobiotic diets and matched omnivorous control infants: a population-based mixed-longitudinal study. I. Weaning pattern, energy and nutrient intake. Eur J Clin Nutr.1989;43:311-23. | Design, DV
127 | Daniels, L. A.,Mallan, K. M.,Battistutta, D.,Nicholson, J. M.,Meedeniya, J. E.,Bayer, J. K.,Magarey, A. Child eating behavior outcomes of an early feeding intervention to reduce risk indicators for child obesity: the NOURISH RCT. Obesity (Silver Spring).2014;22:E104-11. | DV
128 | Daniels, L. A.,Mallan, K. M.,Battistutta, D.,Nicholson, J. M.,Perry, R.,Magarey, A. Evaluation of an intervention to promote protective infant feeding practices to prevent childhood obesity: outcomes of the NOURISH RCT at 14 months of age and 6 months post the first of two intervention modules. Int J Obes (Lond).2012;36:1292-8. | IV, DV
129 | Daniels, L. A.,Mallan, K. M.,Nicholson, J. M.,Battistutta, D.,Magarey, A. Outcomes of an early feeding practices intervention to prevent childhood obesity. Pediatrics.2013;132:e109-18. | IV
130 | Daniels, L. A.,Mallan, K. M.,Nicholson, J. M.,Thorpe, K.,Nambiar, S.,Mauch, C. E.,Magarey, A. An Early Feeding Practices Intervention for Obesity Prevention. Pediatrics.2015;136:e40-9. | IV
131 | Daniels, M. C.,Adair, L. S. Breast-feeding influences cognitive development in Filipino children. J Nutr.2005;135:2589-95. | IV
132 | Davidsson,L.,Sarker,S. A.,Jamil,K. A.,Sultana,S.,Hurrell,R. Regular consumption of a complementary food fortified with ascorbic acid and ferrous fumarate or ferric pyrophosphate is as useful as ferrous sulfate in maintaining hemoglobin concentrations >105 g/L in young Bangladeshi children. Am J Clin Nutr.2009;89:1815-20. | IV, DV
133 | de Hoog ML,van Eijsden M,Stronks K,Gemke RJ,Vrijkotte TG. The role of infant feeding practices in the explanation for ethnic differences in infant growth: the Amsterdam Born Children and their Development study. Br J Nutr.2011;106:1592-601. | Design
134 | de Kanashiro, H. C.,Brown, K. H.,Lopez de Romana, G.,Lopez, T.,Black, R. E. Consumption of food and nutrients by infants in Huascar (Lima), Peru. Am J Clin Nutr.1990;52:995-1004. | DV
135 | de Villiers, A.,Senekal, M. Determinants of growth failure in 12-24-month-old children in a high-density urban slum community in East London, South Africa. Eur J Clin Nutr.2002;56:1231-41. | Country
136 | de Zegher, F.,Sebastiani, G.,Diaz, M.,Sanchez-Infantes, D.,Lopez-Bermejo, A.,Ibanez, L. Body composition and circulating high-molecular-weight adiponectin and IGF-I in infants born small for gestational age: breast- versus formula-feeding. Diabetes.2012;61:1969-73. | Health status, IV
137 | Delport, S. D.,Becker, P. J.,Bergh, A. Growth, feeding practices and infections in black infants. S Afr Med J.1997;87:57-61. | IV, DV
138 | Dewey, K. G.,Cohen, R. J.,Rivera, L. L.,Canahuati, J.,Brown, K. H. Do exclusively breast-fed infants require extra protein?. Pediatr Res.1996;39:303-7. | IV
139 | Dewey, K. G.,Hawck, M. G.,Brown, K. H.,Lartey, A.,Cohen, R. J.,Peerson, J. M. Infant weight-for-length is positively associated with subsequent linear growth across four different populations. Matern Child Nutr.2005;1:11-20. | IV
140 | Dewey, K. G.,Heinig, M. J.,Nommsen, L. A.,Lonnerdal, B. Adequacy of energy intake among breast-fed infants in the DARLING study: relationships to growth velocity, morbidity, and activity levels. Davis Area Research on Lactation, Infant Nutrition and Growth. J Pediatr.1991;119:538-47. | IV
141 | Dewey, K. G.,Lonnerdal, B. Milk and nutrient intake of breast-fed infants from 1 to 6 months: relation to growth and fatness. J Pediatr Gastroenterol Nutr.1983;2:497-506. | IV
142 | Dewey, K. G.,Peerson, J. M.,Brown, K. H.,Krebs, N. F.,Michaelsen, K. F.,Persson, L. A.,Salmenpera, L.,Whitehead, R. G.,Yeung, D. L. Growth of breast-fed infants deviates from current reference data: a pooled analysis of US, Canadian, and European data sets. World Health Organization Working Group on Infant Growth. Pediatrics.1995;96:495-503. | Design
143 | Dewey, K. G.,Peerson, J. M.,Heinig, M. J.,Nommsen, L. A.,Lonnerdal, B.,Lopez de Romana, G.,de Kanashiro, H. C.,Black, R. E.,Brown, K. H. Growth patterns of breast-fed infants in affluent (United States) and poor (Peru) communities: implications for timing of complementary feeding. Am J Clin Nutr.1992;56:1012-8. | IV, DV
144 | Dewey, K. G. Complementary feeding and infant growth and body composition. Pediatrics.2000;106:1281. | Design
145 | Dewey,K. G.,Cohen,R. J.,Brown,K. H.,Rivera,L. L. Effects of exclusive breastfeeding for four versus six months on maternal nutritional status and infant motor development: results of two randomized trials in Honduras. J Nutr.2001;131:262-7. | Country
146 | Dewey,K. G.,Cohen,R. J.,Rivera,L. L.,Brown,K. H. Effects of age of introduction of complementary foods on iron status of breast-fed infants in Honduras. Am J Clin Nutr.1998;67:878-84. | DV
147 | Dewey,K. G.,Huffman,S. L. Maternal, infant, and young child nutrition: combining efforts to maximize impacts on child growth and micronutrient status. Food Nutr Bull.2009;30:S187-9. | Design
148 | Dewey,K. G.,Romero-Abal,M. E.,Quan de Serrano,J.,Bulux,J.,Peerson,J. M.,Eagle,P.,Solomons,N. W. Effects of discontinuing coffee intake on iron status of iron-deficient Guatemalan toddlers: a randomized intervention study. Am J Clin Nutr.1997;66:168-76. | DV
149 | Diaz, S.,Herreros, C.,Aravena, R.,Casado, M. E.,Reyes, M. V.,Schiappacasse, V. Breast-feeding duration and growth of fully breast-fed infants in a poor urban Chilean population. Am J Clin Nutr.1995;62:371-6. | IV, DV
150 | Doak, C. M.,van der Starre, R. E.,van Beusekom, I.,Campos Ponce, M.,Vossenaar, M.,Solomons, N. W. Earlier introduction of aguitas is associated with higher risk of stunting in infants and toddlers in the Western Highlands of Guatemala. Am J Clin Nutr.2013;97:631-6. | Design
151 | Domellof,M.,Cohen,R. J.,Dewey,K. G.,Hernell,O.,Rivera,L. L.,Lonnerdal,B. Iron supplementation of breast-fed Honduran and Swedish infants from 4 to 9 months of age. J Pediatr.2001;138:679-87. | IV, DV
152 | Dong,C.,Ge,P.,Ren,X.,Wang,J.,Fan,H.,Yan,X.,Yin,S. A. Prospective study on the effectiveness of complementary food supplements on improving status of elder infants and young children in the areas affected by Wenchuan earthquake. PLoS One.2013;8:e72711. | Design, Health status
153 | Donma, M. M.,Donma, O. Infant feeding and growth: a study on Turkish infants from birth to 6 months. Pediatr Int.1999;41:542-8. | IV
154 | Donma, M. M.,Donma, O. The influence of feeding patterns on head circumference among Turkish infants during the first 6 months of life. Brain Dev.1997;19:393-7. | IV
155 | Dubakiene, R.,Rudzeviciene, O.,Butiene, I.,Sezaite, I.,Petronyte, M.,Vaicekauskaite, D.,Zvirbliene, A. Studies on early allergic sensitization in the Lithuanian birth cohort. ScientificWorldJournal.2012;2012:909524. | IV, DV
156 | Dubois, L.,Girard, M. Breast-feeding, day-care attendance and the frequency of antibiotic treatments from 1.5 to 5 years: a population-based longitudinal study in Canada. Soc Sci Med.2005;60:2035-44. | IV, DV
157 | Dubois, L.,Girard, M. Social inequalities in infant feeding during the first year of life. The Longitudinal Study of Child Development in Quebec (LSCDQ 1998-2002). Public Health Nutr.2003;6:773-83. | IV, DV
158 | Dubowitz, T.,Levinson, D.,Peterman, J. N.,Verma, G.,Jacob, S.,Schultink, W. Intensifying efforts to reduce child malnutrition in India: an evaluation of the Dular program in Jharkhand, India. Food Nutr Bull.2007;28:266-73. | IV
159 | Duggan,C.,Penny,M. E.,Hibberd,P.,Gil,A.,Huapaya,A.,Cooper,A.,Coletta,F.,Emenhiser,C.,Kleinman,R. E. Oligofructose-supplemented infant cereal: 2 randomized, blinded, community-based trials in Peruvian infants. Am J Clin Nutr.2003;77:937-42. | IV
160 | Dunne,A. Nutrition in infancy: achieving nutrition needs for new mothers and children. Br J Community Nurs.2012;Suppl:S22. | Design
161 | Edmondson, L. What toddlers eat really matters. J Fam Health Care.2011;21:33-41. | Design
162 | El-Sayed H,Martines J,Rakha M,Zekry O,Abdel-Hak M,Abbas H. The effectiveness of the WHO training course on complementary feeding counseling in a primary care setting, Ismailia, Egypt. J Egypt Public Health Assoc.2014;89:1-8. | IV
163 | Elwood, P. C.,Haley, T. J.,Hughes, S. J.,Sweetnam, P. M.,Gray, O. P.,Davies, D. P. Child growth (0-5 years), and the effect of entitlement to a milk supplement. Arch Dis Child.1981;56:831-5. | IV
164 | Emmett,P. M.,Jones,L. R. Diet and growth in infancy: relationship to socioeconomic background and to health and development in the Avon Longitudinal Study of Parents and Children. Nutr Rev.2014;72:483-506. | Design
165 | Emond A,Drewett R,Blair P,Emmett P. Postnatal factors associated with failure to thrive in term infants in the Avon Longitudinal Study of Parents and Children. Arch Dis Child.2007;92:115-9. | IV
166 | Eneroth,H.,El Arifeen,S.,Persson,L. A.,Kabir,I.,Lonnerdal,B.,Hossain,M. B.,Ekstrom,E. C. Duration of exclusive breast-feeding and infant iron and zinc status in rural Bangladesh. J Nutr.2009;139:1562-7. | IV, DV
167 | Engelmann,M. D.,Davidsson,L.,Sandstrom,B.,Walczyk,T.,Hurrell,R. F.,Michaelsen,K. F. The influence of meat on nonheme iron absorption in infants. Pediatr Res.1998;43:768-73. | DV
168 | England, L.,Brenner, R.,Bhaskar, B.,Simons-Morton, B.,Das, A.,Revenis, M.,Mehta, N.,Clemens, J. Breastfeeding practices in a cohort of inner-city women: the role of contraindications. BMC Public Health.2003;3:28. | IV, DV
169 | Escribano, J.,Luque, V.,Ferre, N.,Mendez-Riera, G.,Koletzko, B.,Grote, V.,Demmelmair, H.,Bluck, L.,Wright, A.,Closa-Monasterolo, R. Effect of protein intake and weight gain velocity on body fat mass at 6 months of age: the EU Childhood Obesity Programme. Int J Obes (Lond).2012;36:548-53. | IV
170 | Esfarjani, F.,Azar, M. R.,Gafarpour, M. IDDM and early exposure of infant to cow’s milk and solid food. Indian J Pediatr.2001;68:107-10. | DV
171 | Evans, D.,Hansen, J. D.,Moodie, A. D.,van der Spuy, H. I. Intellectual development and nutrition. J Pediatr.1980;97:358-63. | Health status, IV
172 | Exl, B. M.,Deland, U.,Secretin, M. C.,Preysch, U.,Wall, M.,Shmerling, D. H. Improved general health status in an unselected infant population following an allergen reduced dietary intervention programme. The ZUFF-study-programme. Part I: Study design and 6-month nutritional behaviour. Eur J Nutr.2000;39:89-102. | DV
173 | Exl, B. M.,Deland, U.,Secretin, M. C.,Preysch, U.,Wall, M.,Shmerling, D. H. Improved general health status in an unselected infant population following an allergen-reduced dietary intervention programme: the ZUFF-STUDY-PROGRAMME. Part II: infant growth and health status to age 6 months. ZUg-FrauenFeld. Eur J Nutr.2000;39:145-56. | IV
174 | Faber,M.,Kvalsvig,J. D.,Lombard,C. J.,Benade,A. J. Effect of a fortified maize-meal porridge on anemia, micronutrient status, and motor development of infants. Am J Clin Nutr.2005;82:1032-9. | Country
175 | Faber,M. Dietary intake and anthropometric status differ for anaemic and non-anaemic rural South African infants aged 6-12 months. J Health Popul Nutr.2007;25:285-93. | Design
176 | Fabiansen, C.,Phelan, K. P.,Cichon, B.,Ritz, C.,Briend, A.,Michaelsen, K. F.,Friis, H.,Shepherd, S. Short children with a low midupper arm circumference respond to food supplementation: an observational study from Burkina Faso. Am J Clin Nutr.2016;103:415-21. | Health status
177 | Fabius, R. J.,Merritt, R. J.,Fleiss, P. M.,Ashley, J. M. Malnutrition associated with a formula of barley water, corn syrup, and whole milk. Am J Dis Child.1981;135:615-7. | Design
178 | Falkner, F. Introduction of food to infants. Genetic-environmental considerations. Am J Clin Nutr.1985;41:436-9. | Design
179 | Fall CH,Borja JB,Osmond C,Richter L,Bhargava SK,Martorell R,Stein AD,Barros FC,Victora CG. Infant-feeding patterns and cardiovascular risk factors in young adulthood: data from five cohorts in low- and middle-income countries. Int J Epidemiol.2011;40:47-62. | Design
180 | Farris, R. P.,Frank, G. C.,Webber, L. S.,Srinivasan, S. R.,Berenson, G. S. Influence of milk source on serum lipids and lipoproteins during the first year of life, Bogalusa heart study. Am J Clin Nutr.1982;35:42-9. | IV
181 | Farrow, C. V.,Blissett, J. Controlling feeding practices: cause or consequence of early child weight?. Pediatrics.2008;121:e164-9. | IV
182 | Farrow, C.,Blissett, J. Does maternal control during feeding moderate early infant weight gain?. Pediatrics.2006;118:e293-8. | IV
183 | Fawcett, J. N. Feeding from birth to 18 months. Nursing (Lond).1981:956-8. | Design
184 | Feldens CA,Vitolo MR,Rauber F,Cruz LN,Hilgert JB. Risk factors for discontinuing breastfeeding in southern Brazil: a survival analysis. Matern Child Health J.2012;16:1257-65. | IV, DV
185 | Feldens, C. A.,Ardenghi, T. M.,Cruz, L. N.,Scalco, G. P.,Vitolo, M. R. Advising mothers about breastfeeding and weaning reduced pacifier use in the first year of life: a randomized trial. Community Dent Oral Epidemiol.2013;41:317-26. | IV, DV
186 | Feldens, C. A.,Kramer, P. F.,Sequeira, M. C.,Rodrigues, P. H.,Vitolo, M. R. Maternal education is an independent determinant of cariogenic feeding practices in the first year of life. Eur Arch Paediatr Dent.2012;13:70-5. | DV
187 | Fergusson, D. M.,Woodward, L. J. Breast feeding and later psychosocial adjustment. Paediatr Perinat Epidemiol.1999;13:144-57. | IV
188 | Fernandes, T. A.,Werneck, G. L.,Hasselmann, M. H. Prepregnancy weight, weight gain during pregnancy, and exclusive breastfeeding in the first month of Life in Rio de Janeiro, Brazil. J Hum Lact.2012;28:55-61. | IV, DV
189 | Fernstrom, J. D.,Navia, J. L. Introduction to the workshop. Low-calorie sweeteners and weight control--what the science tells us. J Nutr.2012;142:1132s-3s. | Design
190 | Ferrara,M.,Bertocco,F.,Ricciardi,A.,Ferrara,D.,Incarnato,L.,Capozzi,L. Iron deficiency screening in the first three years of life: a three-decade-long retrospective case study. Hematology.2014;19:239-43. | DV
191 | Fildes, A.,van Jaarsveld, C. H.,Llewellyn, C.,Wardle, J.,Fisher, A. Parental control over feeding in infancy. Influence of infant weight, appetite and feeding method. Appetite.2015;91:101-6. | IV, DV
192 | Fisher, J. O.,Birch, L. L.,Smiciklas-Wright, H.,Picciano, M. F. Breast-feeding through the first year predicts maternal control in feeding and subsequent toddler energy intakes. J Am Diet Assoc.2000;100:641-6. | IV, DV
193 | Flax, V. L.,Bentley, M. E.,Chasela, C. S.,Kayira, D.,Hudgens, M. G.,Kacheche, K. Z.,Chavula, C.,Kourtis, A. P.,Jamieson, D. J.,van der Horst, C. M.,Adair, L. S. Lipid-based nutrient supplements are feasible as a breastmilk replacement for HIV-exposed infants from 24 to 48 weeks of age. J Nutr.2013;143:701-7. | Health status, IV
194 | Fomon SJ,Ziegler EE,Nelson SE,Edwards BB. Sweetness of diet and food consumption by infants. Proc Soc Exp Biol Med.1983;173:190-3. | IV, DV
195 | Fomon, S. J.,Rogers, R. R.,Ziegler, E. E.,Nelson, S. E.,Thomas, L. N. Indices of fatness and serum cholesterol at age eight years in relation to feeding and growth during early infancy. Pediatr Res.1984;18:1233-8. | IV, Date
196 | Forns,J.,Torrent,M.,Garcia-Esteban,R.,Caceres,A.,Pilar Gomila,M.,Martinez,D.,Morales,E.,Julvez,J.,Grimalt,J. O.,Sunyer,J. Longitudinal association between early life socio-environmental factors and attention function at the age 11 years. Environ Res.2012;117:54-9. | IV
197 | Foroushani, A. R.,Mohammad, K.,Mahmoodi, M.,Siassi, F. Effect of breastfeeding on cognitive performance in a British birth cohort. East Mediterr Health J.2010;16:202-8. | IV
198 | Franks, A. J.,Jurgensen, C. Nutrition and health in the first year of life on a Pacific atoll. Observations on Abemama Atoll, Central Pacific. Trans R Soc Trop Med Hyg.1985;79:681-4. | IV, DV
199 | Frederiksen,B. N.,Seifert,J.,Kroehl,M.,Lamb,M. M.,Milne,G. L.,Rewers,M.,Norris,J. M. Timing of solid food introduction is associated with urinary F2-isoprostane concentrations in childhood. Pediatric Research.2015;78:451-456. | DV
200 | Freeman, V.,van’t Hof, M.,Haschke, F. Patterns of milk and food intake in infants from birth to age 36 months: the Euro-growth study. J Pediatr Gastroenterol Nutr.2000;31 Suppl 1:S76-85. | DV
201 | Freeman,V. E.,Mulder,J.,van’t Hof,M. A.,Hoey,H. M.,Gibney,M. J. A longitudinal study of iron status in children at 12, 24 and 36 months. Public Health Nutr.1998;1:93-100. | DV
202 | Friel,J. K.,Andrews,W. L.,Simmons,B. S.,L’Abbe,M. R.,Mercer,C.,MacDonald,A.,McCloy,U. R. Evaluation of full-term infants fed an evaporated milk formula. Acta Paediatr.1997;86:448-53. | IV
203 | Froozani, M. D.,Malekafzali, H.,Bahrini, B. Growth of a group of low income infants in the first year of life. J Trop Pediatr.1980;26:96-8. | Design, IV
204 | Fuchs Iii, G. J.,Gastanaduy, A. S.,Suskind, R. M. Comparative metabolic study of older infants fed infant formula, transition formula, or whole cow’s milk. Nutrition Research.1992;12:1467-1478. | IV
205 | Fuchs, G. J.,Farris, R. P.,DeWier, M.,Hutchinson, S.,Strada, R.,Suskind, R. M. Effect of dietary fat on cardiovascular risk factors in infancy. Pediatrics.1994;93:756-63. | IV
206 | Gabriel, C. G.,Corso, A. C.,Caldeira, G. V.,Gimeno, S. G.,Schmitz Bde, A.,de Vasconcelos Fde, A. Overweight and obesity related factors in schoolchildren in Santa Catarina State, Brazil. Arch Latinoam Nutr.2010;60:332-9. | Design
207 | Gaffney, K. F.,Brito, A. V.,Kitsantas, P.,Kermer, D. A. Early Feeding Practices and Weight Status at One Year of Age: A Comparison of Hispanic Immigrant Mother-Infant Dyads with Participants of the Infant Feeding Practices Study II. Child Obes.2016. | IV, DV
208 | Gale, C.,Thomas, E. L.,Jeffries, S.,Durighel, G.,Logan, K. M.,Parkinson, J. R.,Uthaya, S.,Santhakumaran, S.,Bell, J. D.,Modi, N. Adiposity and hepatic lipid in healthy full-term, breastfed, and formula-fed human infants: a prospective short-term longitudinal cohort study. Am J Clin Nutr.2014;99:1034-40. | IV
209 | Galler, J. R.,Ramsey, F. C.,Harrison, R. H.,Brooks, R.,Weiskopf-Bock, S. Infant feeding practices in Barbados predict later growth. J Nutr.1998;128:1328-35. | IV
210 | Gallo PV. Physiological and behavioral consequences of maternal and post-weaning protein restriction. Physiol Behav.1981;26:77-84. | Design, Health status
211 | Galtry, J. Punching above its weight: does New Zealand’s responsibility for protecting, promoting, and supporting breastfeeding extend beyond its own borders?. J Hum Lact.2013;29:128-31. | Design
212 | Garza, C. The INTERGROWTH-21st project and the multicenter growth reference study: enhanced opportunities for monitoring growth from early pregnancy to 5 years of age. Breastfeed Med.2014;9:341-4. | Design
213 | Geuns, M.,Huisinga, C.,van Staveren, W. A.,Deurenberg, P.,Hautvast, J. G. Intakes of energy, protein and calcium and weaning pattern of a group of Dutch infants aged 6-12 months. Tijdschr Kindergeneeskd.1985;53:50-6. | Design, IV, DV
214 | Ghorashi,Z.,Nezami,N.,Ghalehgolab Behbahan,A.,Ghorashi,S. Supplemental food may not prevent iron-deficiency anemia in infants. Indian J Pediatr.2008;75:1121-4. | DV
215 | Ghosh,S.,Kilaru,A.,Ganapathy,S. Nutrition education and infant growth in rural Indian infants: narrowing the gender gap?. J Indian Med Assoc.2002;100:483-4, 486-8, 490. | IV
216 | Gianni, M. L.,Roggero, P.,Morlacchi, L.,Garavaglia, E.,Piemontese, P.,Mosca, F. Formula-fed infants have significantly higher fat-free mass content in their bodies than breastfed babies. Acta Paediatr.2014;103:e277-81. | IV
217 | Gibson,R. S.,Hotz,C. The adequacy of micronutrients in complementary foods. Pediatrics.2000;106:1298-9. | Design
218 | Gill, D. G.,Vincent, S.,Segal, D. S. Follow-on formula in the prevention of iron deficiency: a multicentre study. Acta Paediatr.1997;86:683-9. | IV
219 | Gillman, M. W.,Rifas-Shiman, S. L.,Camargo, C. A., Jr.,Berkey, C. S.,Frazier, A. L.,Rockett, H. R.,Field, A. E.,Colditz, G. A. Risk of overweight among adolescents who were breastfed as infants. Jama.2001;285:2461-7. | Design
220 | Gokcay, G.,Turan, J. M.,Partalci, A.,Neyzi, O. Growth of infants during the first year of life according to feeding regimen in the first 4 months. J Trop Pediatr.2003;49:6-12. | IV
221 | Golley,R. K.,Smithers,L. G.,Mittinty,M. N.,Brazionis,L.,Emmett,P.,Northstone,K.,Campbell,K.,McNaughton,S. A.,Lynch,J. W. An index measuring adherence to complementary feeding guidelines has convergent validity as a measure of infant diet quality. J Nutr.2012;142:901-8. | IV, DV
222 | Gomez Santos, S. F.,Estevez Santiago, R.,Palacios Gil-Antunano, N.,Leis Trabazo, M. R.,Tojo Sierra, R.,Cuadrado Vives, C.,Beltran de Miguel, B.,Avila Torres, J. M.,Varela Moreiras, G.,Casas Esteve, R. THAO-CHILD HEALTH PROGRAMME: COMMUNITY BASED INTERVENTION FOR HEALTHY LIFESTYLES PROMOTION TO CHILDREN AND FAMILIES: RESULTS OF A COHORT STUDY. Nutr Hosp.2015;32:2584-7. | Age
223 | Gomez-Sanchiz, M.,Canete, R.,Rodero, I.,Baeza, J. E.,Avila, O. Influence of breast-feeding on mental and psychomotor development. Clin Pediatr (Phila).2003;42:35-42. | IV
224 | Gomez-Sanchiz, M.,Canete, R.,Rodero, I.,Baeza, J. E.,Gonzalez, J. A. Influence of breast-feeding and parental intelligence on cognitive development in the 24-month-old child. Clin Pediatr (Phila).2004;43:753-61. | IV
225 | Gong, Y. H.,Ji, C. Y.,Zheng, X. X.,Shan, J. P.,Hou, R. Correlation of 4-month infant feeding modes with their growth and iron status in Beijing. Chin Med J (Engl).2008;121:392-8. | IV
226 | Gooze, R. A.,Anderson, S. E.,Whitaker, R. C. Prolonged bottle use and obesity at 5.5 years of age in US children. J Pediatr.2011;159:431-6. | IV
227 | Greene, L. C.,Lucas, A.,Livingstone, M. B.,Harland, P. S.,Baker, B. A. Relationship between early diet and subsequent cognitive performance during adolescence. Biochem Soc Trans.1995;23:376s. | Design, IV
228 | Greer,F. R.,Searcy,J. E.,Levin,R. S.,Steichen,J. J.,Steichen-Asche,P. S.,Tsang,R. C. Bone mineral content and serum 25-hydroxyvitamin D concentrations in breast-fed infants with and without supplemental vitamin D: one-year follow-up. J Pediatr.1982;100:919-22. | IV
229 | Grote, V.,von Kries, R.,Closa-Monasterolo, R.,Scaglioni, S.,Gruszfeld, D.,Sengier, A.,Langhendries, J. P.,Koletzko, B. Protein intake and growth in the first 24 months of life. J Pediatr Gastroenterol Nutr.2010;51 Suppl 3:S117-8. | Design, IV
230 | Gruszfeld, D.,Weber, M.,Nowakowska-Rysz, M.,Janas, R.,Kozlik-Feldmann, R.,Xhonneux, A.,Carlier, C.,Riva, E.,Verduci, E.,Closa-Monasterolo, R.,Escribano, J.,Dobrzanska, A.,Koletzko, B. Protein intake in infancy and carotid intima media thickness at 5 years--a secondary analysis from a randomized trial. Ann Nutr Metab.2015;66:51-9. | IV
231 | Gubbels, J. S.,Thijs, C.,Stafleu, A.,van Buuren, S.,Kremers, S. P. Association of breast-feeding and feeding on demand with child weight status up to 4 years. Int J Pediatr Obes.2011;6:e515-22. | IV, DV
232 | Gunderson, E. P.,Hurston, S. R.,Dewey, K. G.,Faith, M. S.,Charvat-Aguilar, N.,Khoury, V. C.,Nguyen, V. T.,Quesenberry, C. P., Jr. The study of women, infant feeding and type 2 diabetes after GDM pregnancy and growth of their offspring (SWIFT Offspring study): prospective design, methodology and baseline characteristics. BMC Pregnancy Childbirth.2015;15:150. | Design
233 | Gunnarsdottir I,Schack-Nielsen L,Michaelsen KF,Sorensen TI,Thorsdottir I. Infant weight gain, duration of exclusive breast-feeding and childhood BMI - two similar follow-up cohorts. Public Health Nutr.2010;13:201-7. | IV
234 | Gunnarsdottir, I.,Thorsdottir, I. Relationship between growth and feeding in infancy and body mass index at the age of 6 years. Int J Obes Relat Metab Disord.2003;27:1523-7. | IV
235 | Gunther, A. L.,Buyken, A. E.,Kroke, A. Protein intake during the period of complementary feeding and early childhood and the association with body mass index and percentage body fat at 7 y of age. Am J Clin Nutr.2007;85:1626-33. | IV
236 | Gunther, A. L.,Buyken, A. E.,Kroke, A. The influence of habitual protein intake in early childhood on BMI and age at adiposity rebound: results from the DONALD Study. Int J Obes (Lond).2006;30:1072-9. | IV
237 | Gurnida, D. A.,Rowan, A. M.,Idjradinata, P.,Muchtadi, D.,Sekarwana, N. Association of complex lipids containing gangliosides with cognitive development of 6-month-old infants. Early Hum Dev.2012;88:595-601. | IV
238 | Hamilton, K.,Daniels, L.,White, K. M.,Murray, N.,Walsh, A. Predicting mothers’ decisions to introduce complementary feeding at 6 months. An investigation using an extended theory of planned behaviour. Appetite.2011;56:674-81. | IV, DV
239 | Hammer, L. D.,Bryson, S.,Agras, W. S. Development of feeding practices during the first 5 years of life. Arch Pediatr Adolesc Med.1999;153:189-94. | DV
240 | Han,Y. H.,Yon,M.,Han,H. S.,Johnston,K. E.,Tamura,T.,Hyun,T. Zinc status and growth of Korean infants fed human milk, casein-based, or soy-based formula: three-year longitudinal study. Nutr Res Pract.2011;5:46-51. | IV
241 | Harbild, H. L.,Harslof, L. B.,Christensen, J. H.,Kannass, K. N.,Lauritzen, L. Fish oil-supplementation from 9 to 12 months of age affects infant attention in a free-play test and is related to change in blood pressure. Prostaglandins Leukot Essent Fatty Acids.2013;89:327-33. | IV
242 | Harit D,Faridi MM,Aggarwal A,Sharma SB. Lipid profile of term infants on exclusive breastfeeding and mixed feeding: a comparative study. Eur J Clin Nutr.2008;62:203-9. | IV
243 | Harrington,M.,Hotz,C.,Zeder,C.,Polvo,G. O.,Villalpando,S.,Zimmermann,M. B.,Walczyk,T.,Rivera,J. A.,Hurrell,R. F. A comparison of the bioavailability of ferrous fumarate and ferrous sulfate in non-anemic Mexican women and children consuming a sweetened maize and milk drink. Eur J Clin Nutr.2011;65:20-5. | IV, DV
244 | Harris,R. Inadequate diets: short- and long-term problems. J Fam Health Care.2002;12:6. | Design
245 | Hasan,J.,Ray,J.,Khan,Z. Role of weaning in the nutritional status of infant--a longitudinal study in the rural area of Aligarh. J Indian Med Assoc.1996;94:169, 215. | Design, IV, DV
246 | Haschke, F.,Pietschnig, B.,Vanura, H.,Heil, M.,Steffan, I.,Hobiger, G.,Schuster, E.,Camaya, Z. Iron intake and iron nutritional status of infants fed iron-fortified beikost with meat. Am J Clin Nutr.1988;47:108-12. | IV
247 | Hawley, N. L.,Johnson, W.,Nu’usolia, O.,McGarvey, S. T. The contribution of feeding mode to obesogenic growth trajectories in American Samoan infants. Pediatr Obes.2014;9:e1-e13. | IV
248 | Hay,G.,Johnston,C.,Whitelaw,A.,Trygg,K.,Refsum,H. Folate and cobalamin status in relation to breastfeeding and weaning in healthy infants. Am J Clin Nutr.2008;88:105-14. | DV
249 | Hediger, M. L.,Overpeck, M. D.,Ruan, W. J.,Troendle, J. F. Early infant feeding and growth status of US-born infants and children aged 4-71 mo: analyses from the third National Health and Nutrition Examination Survey, 1988-1994. Am J Clin Nutr.2000;72:159-67. | Design, IV
250 | Hegar, B.,Dewanti, N. R.,Kadim, M.,Alatas, S.,Firmansyah, A.,Vandenplas, Y. Natural evolution of regurgitation in healthy infants. Acta Paediatr.2009;98:1189-93. | IV, DV
251 | Heine, W.,Lapsien, C. Influence of early breast milk and formula feeding on body weight in children born in Rostock since 1945. Bibl Nutr Dieta.1982:17-8. | Design
252 | Herbst, A.,Diethelm, K.,Cheng, G.,Alexy, U.,Icks, A.,Buyken, A. E. Direction of associations between added sugar intake in early childhood and body mass index at age 7 years may depend on intake levels. J Nutr.2011;141:1348-54. | IV
253 | Hess,S. Y.,Abbeddou,S.,Jimenez,E. Y.,Somé,J. W.,Vosti,S. A.,Ouédraogo,Z. P.,Guissou,R. M.,Ouédraogo,J. B.,Brown,K. H. Small-quantity lipid-based nutrient supplements, regardless of their zinc content, increase growth and reduce the prevalence of stunting and Wasting in young burkinabe children: A cluster-randomized trial. PLoS ONE.2015;10. | IV, Country
254 | Hettiarachchi,M.,Lekamwasam,S.,Liyanage,C. Long-term cereal-based nutritional supplementation improved the total spine bone mineral density amongst Sri Lankan preschool children: a randomized controlled study. J Pediatr Endocrinol Metab.2010;23:555-63. | IV, Age
255 | Hijazi, S. S.,Abulaban, A.,Waterlow, J. C. The duration for which exclusive breast-feeding is adequate. A study in Jordan. Acta Paediatr Scand.1989;78:23-8. | IV
256 | Hillis, S. D.,Weigle, K.,Miranda, C. M.,McCann, M.,Bender, D.,Stewart, P. Supplementary feeding in Colombian child-care centers and growth velocity. Pediatrics.1994;94:1066-9. | IV
257 | Hitchcock, N. E.,Gracey, M.,Gilmour, A. I. The growth of breast fed and artificially fed infants from birth to twelve months. Acta Paediatr Scand.1985;74:240-5. | IV
258 | Hitchcock, N. E.,McGuiness, D.,Gracey, M. Growth and feeding practices of Western Australian infants. Med J Aust.1982;1:372-6. | Design, IV, DV, Date
259 | Hitchcock, N. E.,Owles, E. N.,Gracey, M. Breast feeding and growth of healthy infants. Med J Aust.1981;2:536-7. | IV, DV, Date
260 | Hoffman, D. R.,Garfield, S.,Morale, S. E.,Bosworth, R. G.,Castaneda, Y. S.,Wheaton, D. K. H.,Theuer, R. C.,Birch, E. E. Visual and neural development of breast-fed infants receiving docosahexaenoic acid (dha)-enriched baby food: a randomized clinical trial. Iovs.2004;45:ARVO E-abstract 3510. | Design
261 | Hokama,T. Levels of serum ferritin and total body iron among infants with different feeding regimens. Acta Paediatr Jpn.1993;35:298-301. | IV, DV
262 | Holgerson PL,Vestman NR,Claesson R,Ohman C,Domellof M,Tanner AC,Hernell O,Johansson I. Oral microbial profile discriminates breast-fed from formula-fed infants. J Pediatr Gastroenterol Nutr.2013;56:127-36. | Design, IV, DV
263 | Hop le, T.,Berger, J. Multiple micronutrient supplementation improves anemia, micronutrient nutrient status, and growth of Vietnamese infants: double-blind, randomized, placebo-controlled trial. J Nutr.2005;135:660s-665s. | IV
264 | Hop, L. T.,Gross, R.,Giay, T.,Sastroamidjojo, S.,Schultink, W.,Lang, N. T. Premature complementary feeding is associated with poorer growth of vietnamese children. J Nutr.2000;130:2683-90. | Country
265 | Hop, L. T.,Gross, R.,Giay, T.,Schultink, W.,Thuan, B. T.,Sastroamidjojo, S. Longitudinal observation of growth of Vietnamese children in Hanoi, Vietnam from birth to 10 years of age. Eur J Clin Nutr.1997;51:164-71. | IV, DV
266 | Hopkins, D.,Steer, C. D.,Northstone, K.,Emmett, P. M. Effects on childhood body habitus of feeding large volumes of cow or formula milk compared with breastfeeding in the latter part of infancy. Am J Clin Nutr.2015;102:1096-103. | IV
267 | Hopkins,D.,Emmett,P.,Steer,C.,Rogers,I.,Noble,S.,Emond,A. Infant feeding in the second 6 months of life related to iron status: an observational study. Arch Dis Child.2007;92:850-4. | DV
268 | Hoppe, C.,Molgaard, C.,Thomsen, B. L.,Juul, A.,Michaelsen, K. F. Protein intake at 9 mo of age is associated with body size but not with body fat in 10-y-old Danish children. Am J Clin Nutr.2004;79:494-501. | IV
269 | Horodynski, M. A.,Baker, S.,Van Egeren, L.,Olson, B.,Brophy-Herb, H.,Auld, G. The healthy babies curriculum. J Nutr Educ Behav.2014;46:151-2. | Design, IV
270 | Horta, B. L.,Bas, A.,Bhargava, S. K.,Fall, C. H.,Feranil, A.,de Kadt, J.,Martorell, R.,Richter, L. M.,Stein, A. D.,Victora, C. G. Infant feeding and school attainment in five cohorts from low- and middle-income countries. PLoS One.2013;8:e71548. | Design
271 | Horwood, L. J.,Fergusson, D. M. Breastfeeding and later cognitive and academic outcomes. Pediatrics.1998;101:E9. | IV
272 | Hosaka, M.,Asayama, K.,Staessen, J. A.,Ohkubo, T.,Hayashi, K.,Tatsuta, N.,Kurokawa, N.,Satoh, M.,Hashimoto, T.,Hirose, T.,Obara, T.,Metoki, H.,Inoue, R.,Kikuya, M.,Nakai, K.,Imai, Y.,Satoh, H. Breastfeeding leads to lower blood pressure in 7-year-old Japanese children: Tohoku Study of Child Development. Hypertens Res.2013;36:117-22. | IV, DV
273 | Hudara S,Mimouni F,Rachman Y,Dayan B,Silbermintz A,Turner D. Retrospective cohort study of a new infant formula during the first 6 months of life: reflections on growth curves, human milk and formula feeding. Isr Med Assoc J.2010;12:676-80. | IV
274 | Hurley, K. M.,Black, M. M. Introduction to a supplement on responsive feeding: promoting healthy growth and development for infants and toddlers. J Nutr.2011;141:489. | Design
275 | Husaini, M. A.,Karyadi, L.,Husaini, Y. K.,Sandjaja,,Karyadi, D.,Pollitt, E. Developmental effects of short-term supplementary feeding in nutritionally-at-risk Indonesian infants. Am J Clin Nutr.1991;54:799-804. | Country
276 | Inostroza, J.,Haschke, F.,Steenhout, P.,Grathwohl, D.,Nelson, S. E.,Ziegler, E. E. Low-protein formula slows weight gain in infants of overweight mothers. J Pediatr Gastroenterol Nutr.2014;59:70-7. | IV
277 | Isherwood,R. J.,Dimond,C.,Longhurst,S. Breast feeding and weaning practices in relation to nutritional status of under-5 children in north Bangladesh. J Trop Pediatr.1988;34:28-31. | Design
278 | Islam, M. M.,Peerson, J. M.,Ahmed, T.,Dewey, K. G.,Brown, K. H. Effects of varied energy density of complementary foods on breast-milk intakes and total energy consumption by healthy, breastfed Bangladeshi children. Am J Clin Nutr.2006;83:851-8. | IV, DV
279 | Jackson, D. A.,Imong, S. M.,Wongsawasdii, L.,Silprasert, A.,Preunglampoo, S.,Leelapat, P.,Drewett, R. F.,Amatayakul, K.,Baum, J. D. Weaning practices and breast-feeding duration in Northern Thailand. Br J Nutr.1992;67:149-64. | IV, DV
280 | Jackson,M. I. Early childhood WIC participation, cognitive development and academic achievement. Soc Sci Med.2015;126:145-53. | IV
281 | Jacobson, S. W.,Chiodo, L. M.,Jacobson, J. L. Breastfeeding effects on intelligence quotient in 4- and 11-year-old children. Pediatrics.1999;103:e71. | IV
282 | Jain,V.,Klein,B. P.,Nash,M.,Chapman-Novakofski,K. Two feasibility studies for introduction of multimicronutrient soy/whey-based supplements in rural homes in Honduras. Journal of Hunger and Environmental Nutrition.2011;6:247-263. | IV
283 | Jansen,G.R.,O’B Hourihane. The nutritional status of preschool children in Egypt. World Rev Nutr Diet.1985;45:42-67. | Design
284 | Jatanasen,A.,Sacholvicharn,V.,Ongkulna,P. An evaluation of supplementary feedings of Thai infants in urban slum communities: effect on growth, health and nutritional status. J Med Assoc Thai.1983;66 Suppl 1:20-9. | Design, Health status
285 | Jensen, B. W.,Nichols, M.,Allender, S.,de Silva-Sanigorski, A.,Millar, L.,Kremer, P.,Lacy, K.,Swinburn, B. Inconsistent associations between sweet drink intake and 2-year change in BMI among Victorian children and adolescents. Pediatr Obes.2013;8:271-83. | Age
286 | Jensen, S. M.,Ritz, C.,Ejlerskov, K. T.,Molgaard, C.,Michaelsen, K. F. Infant BMI peak, breastfeeding, and body composition at age 3 y. Am J Clin Nutr.2015;101:319-25. | IV
287 | Jensen,C. L.,Prager,T. C.,Zou,Y.,Fraley,J. K.,Maude,M.,Anderson,R. E.,Heird,W. C. Effects of maternal docosahexaenoic acid supplementation on visual function and growth of breast-fed term infants. Lipids.1999;34 Suppl:S225. | Design, IV
288 | Jones, G.,Hynes, K. L.,Dwyer, T. The association between breastfeeding, maternal smoking in utero, and birth weight with bone mass and fractures in adolescents: a 16-year longitudinal study. Osteoporos Int.2013;24:1605-11. | IV
289 | Jones, G.,Riley, M.,Dwyer, T. Breastfeeding in early life and bone mass in prepubertal children: a longitudinal study. Osteoporos Int.2000;11:146-52. | IV
290 | Jooste, P. L.,Rossouw, L. J.,Steenkamp, H. J.,Rossouw, J. E.,Swanepoel, A. S.,Charlton, D. O. Effect of breast feeding on the plasma cholesterol and growth of infants. J Pediatr Gastroenterol Nutr.1991;13:139-42. | IV
291 | Joseph, N.,Unnikrishnan, B.,Naik, V. A.,Mahantshetti, N. S.,Mallapur, M. D.,Kotian, S. M.,Nelliyanil, M. Infant rearing practices in South India: a longitudinal study. J Family Med Prim Care.2013;2:37-43. | Country
292 | Joshi N,Agho KE,Dibley MJ,Senarath U,Tiwari K. Determinants of inappropriate complementary feeding practices in young children in Nepal: secondary data analysis of Demographic and Health Survey 2006. Matern Child Nutr.2012;8 Suppl 1:45-59. | Design, Country
293 | Juez, G.,Diaz, S.,Casado, M. E.,Duran, E.,Salvatierra, A. M.,Peralta, O.,Croxatto, H. B. Growth pattern of selected urban Chilean infants during exclusive breast-feeding. Am J Clin Nutr.1983;38:462-8. | IV
294 | Jung, E.,Czajka-Narins, D. M. Birth weight doubling and tripling times: an updated look at the effects of birth weight, sex, race and type of feeding. Am J Clin Nutr.1985;42:182-9. | IV
295 | Kagura, J.,Feeley, A. B.,Micklesfield, L. K.,Pettifor, J. M.,Norris, S. A. Association between infant nutrition and anthropometry, and pre-pubertal body composition in urban South African children. J Dev Orig Health Dis.2012;3:415-23. | Country
296 | Kainonen E,Rautava S,Isolauri E. Immunological programming by breast milk creates an anti-inflammatory cytokine milieu in breast-fed infants compared to formula-fed infants. Br J Nutr.2013;109:1962-70. | IV, DV
297 | Kajantie, E.,Barker, D. J.,Osmond, C.,Forsen, T.,Eriksson, J. G. Growth before 2 years of age and serum lipids 60 years later: the Helsinki Birth Cohort study. Int J Epidemiol.2008;37:280-9. | DV
298 | Kallio, M. J.,Salmenpera, L.,Siimes, M. A.,Perheentupa, J.,Miettinen, T. A. Tracking of serum cholesterol and lipoprotein levels from the first year of life. Pediatrics.1993;91:949-54. | IV, DV
299 | Kallio,M. J.,Salmenpera,L.,Siimes,M. A.,Perheentupa,J.,Miettinen,T. A. Exclusive breast-feeding and weaning: effect on serum cholesterol and lipoprotein concentrations in infants during the first year of life. Pediatrics.1992;89:663-6. | IV, DV
300 | Karaolis-Danckert, N.,Buyken, A. E.,Kulig, M.,Kroke, A.,Forster, J.,Kamin, W.,Schuster, A.,Hornberg, C.,Keil, T.,Bergmann, R. L.,Wahn, U.,Lau, S. How pre- and postnatal risk factors modify the effect of rapid weight gain in infancy and early childhood on subsequent fat mass development: results from the Multicenter Allergy Study 90. Am J Clin Nutr.2008;87:1356-64. | IV
301 | Karlsland Akeson, P. K.,Axelsson, I. E.,Raiha, N. C.,Warm, A.,Minoli, I.,Moro, G. Protein intake and metabolism in formula-fed infants given Swedish or Italian weaning foods. Acta Paediatr.2000;89:158-64. | IV
302 | Karlsson Videhult, F.,Ohlund, I.,Stenlund, H.,Hernell, O.,West, C. E. Probiotics during weaning: a follow-up study on effects on body composition and metabolic markers at school age. Eur J Nutr.2015;54:355-63. | IV
303 | Kattelmann,K. K.,Ho,M.,Specker,B. L. Effect of timing of introduction of complementary foods on iron and zinc status of formula fed infants at 12, 24, and 36 months of age. J Am Diet Assoc.2001;101:443-7. | DV
304 | Kavanagh, K. F.,Cohen, R. J.,Heinig, M. J.,Dewey, K. G. Educational intervention to modify bottle-feeding behaviors among formula-feeding mothers in the WIC program: impact on infant formula intake and weight gain. J Nutr Educ Behav.2008;40:244-50. | IV
305 | Kavle, J. A.,Flax, V. L.,Abdelmegeid, A.,Salah, F.,Hafez, S.,Ramzy, M.,Hamed, D.,Saleh, G.,Galloway, R. Factors associated with early growth in Egyptian infants: implications for addressing the dual burden of malnutrition. Matern Child Nutr.2016;12:139-51. | Country
306 | Kersting, M.,Alexy, U.,Sichert-Hellert, W.,Manz, F.,Schoch, G. Measured consumption of commercial infant food products in German infants: results from the DONALD study. Dortmund Nutritional and Anthropometrical Longitudinally Designed. J Pediatr Gastroenterol Nutr.1998;27:547-52. | DV
307 | Kesaree, N.,Shivamurty, K. S.,Prakash, B. S.,Ramachandra,,Haridas, C. K. Feeding pattern of infants in Devangere. Indian J Pediatr.1981;48:281-4. | Design, IV
308 | Khaldi, F.,Bouguerra, F. Feeding practices, growth, and morbidity in Tunisia. Pediatrics.2000;106:1275-6. | Design, Date
309 | Khan, A. I.,Kabir, I.,Hawkesworth, S.,Ekström, E. C.,Arifeen, S.,Frongillo, E. A.,Persson, L. A. Early invitation to food and/or multiple micronutrient supplementation in pregnancy does not affect body composition in offspring at 54 months: Follow-up of the MINIMat randomised trial, Bangladesh. Maternal and Child Nutrition.2015;11:385-397. | IV, Age
310 | Khan, M. U. Breastfeeding, growth and diarrhoea in rural Bangladesh children. Hum Nutr Clin Nutr.1984;38:113-9. | IV
311 | Khan, M. Infant feeding practices in rural Meheran, Comilla, Bangladesh. Am J Clin Nutr.1980;33:2356-64. | IV, DV
312 | Kholdi N,Zayeri F,Bagheban AA,Khodakarim S,Ramezankhani A. A study of growth failure and its related factors in children from 0 to 2 years in Tehran, Iran. Turk J Pediatr.2012;54:38-44. | Design
313 | Kiefte-de Jong, J. C.,de Vries, J. H.,Escher, J. C.,Jaddoe, V. W.,Hofman, A.,Raat, H.,Moll, H. A. Role of dietary patterns, sedentary behaviour and overweight on the longitudinal development of childhood constipation: the Generation R study. Matern Child Nutr.2013;9:511-23. | DV
314 | Kilaru, A.,Griffiths, P. L.,Ganapathy, S.,Ghosh, S. Community-based nutrition education for improving infant growth in rural Karnataka. Indian Pediatr.2005;42:425-32. | IV
315 | King,S.,Prawitz,A. D.,Umoren,J.,O’Gorman,T. The impact of high diastase malted barley flour on weight and height of malnourished children in Panama. Journal of Hunger and Environmental Nutrition.2007;1:23-35. | Health status, Age
316 | Klag, E. A.,McNamara, K.,Geraghty, S. R.,Keim, S. A. Associations Between Breast Milk Feeding, Introduction of Solid Foods, and Weight Gain in the First 12 Months of Life. Clin Pediatr (Phila).2015;54:1059-67. | Design
317 | Kleinman, R. E. Complementary feeding and neuromuscular development. Pediatrics.2000;106:1279. | Design
318 | Kolacek, S.,Kapetanovic, T.,Zimolo, A.,Luzar, V. Early determinants of cardiovascular risk factors in adults. A. Plasma lipids. Acta Paediatr.1993;82:699-704. | DV
319 | Koletzko, B.,Dokoupil, K.,Reitmayr, S.,Weimert-Harendza, B.,Keller, E. Dietary fat intakes in infants and primary school children in Germany. Am J Clin Nutr.2000;72:1392s-1398s. | IV, DV
320 | Koletzko, B.,von Kries, R.,Closa, R.,Escribano, J.,Scaglioni, S.,Giovannini, M.,Beyer, J.,Demmelmair, H.,Anton, B.,Gruszfeld, D.,Dobrzanska, A.,Sengier, A.,Langhendries, J. P.,Rolland Cachera, M. F.,Grote, V. Can infant feeding choices modulate later obesity risk?. Am J Clin Nutr.2009;89:1502s-1508s. | Design, IV
321 | Koletzko, B.,von Kries, R.,Closa, R.,Escribano, J.,Scaglioni, S.,Giovannini, M.,Beyer, J.,Demmelmair, H.,Gruszfeld, D.,Dobrzanska, A.,Sengier, A.,Langhendries, J. P.,Rolland Cachera, M. F.,Grote, V. Lower protein in infant formula is associated with lower weight up to age 2 y: a randomized clinical trial. Am J Clin Nutr.2009;89:1836-45. | IV
322 | Koletzko, B. Complementary foods and the development of food allergy. Pediatrics.2000;106:1285. | Design
323 | Konstantynowicz, J.,Nguyen, T. V.,Kaczmarski, M.,Jamiolkowski, J.,Piotrowska-Jastrzebska, J.,Seeman, E. Fractures during growth: potential role of a milk-free diet. Osteoporos Int.2007;18:1601-7. | Age
324 | Kramer, M. S.,Fombonne, E.,Matush, L.,Bogdanovich, N.,Dahhou, M.,Platt, R. W. Long-term behavioural consequences of infant feeding: the limits of observational studies. Paediatr Perinat Epidemiol.2011;25:500-6. | IV
325 | Kramer, M. S.,Guo, T.,Platt, R. W.,Shapiro, S.,Collet, J. P.,Chalmers, B.,Hodnett, E.,Sevkovskaya, Z.,Dzikovich, I.,Vanilovich, I. Breastfeeding and infant growth: biology or bias?. Pediatrics.2002;110:343-7. | IV
326 | Kramer, M. S.,Moodie, E. E.,Dahhou, M.,Platt, R. W. Breastfeeding and infant size: evidence of reverse causality. Am J Epidemiol.2011;173:978-83. | IV, DV
327 | Kramer, M. S.,Moodie, E. E.,Platt, R. W. Infant feeding and growth: can we answer the causal question?. Epidemiology.2012;23:790-4. | Design
328 | Kramer, M. S. Do breast-feeding and delayed introduction of solid foods protect against subsequent obesity?. J Pediatr.1981;98:883-7. | Design
329 | Krebs,N. F. Culbertson D. L. Westcott J. L. Sherlock L. Hambidge K. M. Normal Iron Status in Breastfed Infants Consuming Meat as an Early Complementary Food. Pediatric Academic Societies Annual Meeting.2011. | Design
330 | Krebs,N. F.,Hambidge,K. M.,Westcott,J. E.,Miller,L. V.,Sian,L.,Bell,M.,Grunwald,G. Exchangeable zinc pool size in infants is related to key variables of zinc homeostasis. J Nutr.2003;133:1498s-501s. | DV
331 | Krebs,N. F.,Mazariegos,M.,Chomba,E.,Sami,N.,Pasha,O.,Tshefu,A.,Carlo,W. A.,Goldenberg,R. L.,Bose,C. L.,Wright,L. L.,Koso-Thomas,M.,Goco,N.,Kindem,M.,McClure,E. M.,Westcott,J.,Garces,A.,Lokangaka,A.,Manasyan,A.,Imenda,E.,Hartwell,T. D.,Hambidge,K. M. Randomized controlled trial of meat compared with multimicronutrient-fortified cereal in infants and toddlers with high stunting rates in diverse settings. Am J Clin Nutr.2012;96:840-7. | Country
332 | Krebs,N. F.,Westcott,J. E.,Culbertson,D. L.,Sian,L.,Miller,L. V.,Hambidge,K. M. Comparison of complementary feeding strategies to meet zinc requirements of older breastfed infants. Am J Clin Nutr.2012;96:30-5. | DV
333 | Kronborg, H.,Foverskov, E.,Vaeth, M. Predictors for early introduction of solid food among Danish mothers and infants: an observational study. BMC Pediatr.2014;14:243. | Design, DV
334 | Kuklina, E. V.,Ramakrishnan, U.,Stein, A. D.,Barnhart, H. H.,Martorell, R. Growth and diet quality are associated with the attainment of walking in rural Guatemalan infants. J Nutr.2004;134:3296-300. | IV
335 | Kumar, V.,Sharma, S.,Khanna, P.,Vanaja, K. Breast vs bottle feeding-impact on growth in urban infants. Indian J Pediatr.1981;48:271-5. | IV, DV
336 | Kusin, J. A.,Kardjati, S.,van Steenbergen, W. M.,Renqvist, U. H. Nutritional transition during infancy in East Java, Indonesia: 2. A longitudinal study of growth in relation to the intake of breast milk and additional foods. Eur J Clin Nutr.1991;45:77-84. | IV
337 | Kusin, J. A.,Kardjati, S.,van Steenbergen, W. Traditional infant feeding practices: right or wrong?. Soc Sci Med.1985;21:283-6. | IV, Country
338 | Kwok, M. K.,Leung, G. M.,Lam, T. H.,Schooling, C. M. Breastfeeding, childhood milk consumption, and onset of puberty. Pediatrics.2012;130:e631-9. | DV
339 | Laitinen,K.,Kalliomaki,M.,Poussa,T.,Lagstrom,H.,Isolauri,E. Evaluation of diet and growth in children with and without atopic eczema: follow-up study from birth to 4 years. Br J Nutr.2005;94:565-74. | IV, DV
340 | Lampe,J. B.,Velez,N. The effect of prolonged bottle feeding on cow’s milk intake and iron stores at 18 months of age. Clin Pediatr (Phila).1997;36:569-72. | Design
341 | Lang B,Moynihan P. The weaning diet: promoting growth while safeguarding dental health. Quintessence Int.2006;37:632-6. | Design
342 | Larnkjaer, A.,Hoppe, C.,Molgaard, C.,Michaelsen, K. F. The effects of whole milk and infant formula on growth and IGF-I in late infancy. Eur J Clin Nutr.2009;63:956-63. | IV
343 | Lasky, P. A.,Eichelberger, K. M. Implications, considerations, and nursing interventions of obesity in neonatal and preschool patients. Nurs Clin North Am.1982;17:199-205. | Design
344 | Lauzon-Guillain, Bd,Wijndaele, K.,Clark, M.,Acerini, C. L.,Hughes, I. A.,Dunger, D. B.,Wells, J. C.,Ong, K. K. Breastfeeding and infant temperament at age three months. PLoS One.2012;7:e29326. | Design, IV
345 | Lawlor, D. A.,Riddoch, C. J.,Page, A. S.,Andersen, L. B.,Wedderkopp, N.,Harro, M.,Stansbie, D.,Smith, G. D. Infant feeding and components of the metabolic syndrome: findings from the European Youth Heart Study. Arch Dis Child.2005;90:582-8. | IV
346 | Lee, K. Crying and behavior pattern in breast- and formula-fed infants. Early Hum Dev.2000;58:133-40. | Design, IV, DV
347 | Leermakers, E. T.,Kiefte-de Jong, J. C.,Hofman, A.,Jaddoe, V. W.,Franco, O. H. Lutein intake at the age of 1 year and cardiometabolic health at the age of 6 years: the Generation R Study. Br J Nutr.2015;114:970-8. | IV
348 | Legovic, M.,Ostric, L. The effects of feeding methods on the growth of the jaws in infants. ASDC J Dent Child.1991;58:253-5. | Design, IV, DV
349 | Lei, D. L.,Chaves, S. P.,Paes, A. T.,Escuder, M. M.,Ribeiro, A. B.,Freire, R. D.,Lerner, B. R. Risk of linear growth retardation during the first two years of life: a new approach. Eur J Clin Nutr.1999;53:456-60. | IV
350 | Leonard, W. R.,Dewalt, K. M.,Stansbury, J. P.,McCaston, M. K. Influence of dietary quality on the growth of highland and coastal Ecuadorian children. Am J Hum Biol.2000;12:825-837. | IV
351 | Leroy, J. L.,Ruel, M.,Habicht, J. P.,Frongillo, E. A. Using height-for-age differences (HAD) instead of height-for-age z-scores (HAZ) for the meaningful measurement of population-level catch-up in linear growth in children less than 5 years of age. BMC Pediatr.2015;15:145. | IV
352 | Leung, S. S.,Peng, C. X.,Xu, Y. Y.,Liu, K. M.,Quan, X. J.,Lui, S.,Davies, D. P. Comparative study of growth of Chinese infants: Hong Kong versus Guangzhou. J Trop Pediatr.1994;40:166-71. | IV, DV
353 | Leung,S.,Davies,D. P. Infant feeding and growth of Chinese infants: birth to 2 years. Paediatr Perinat Epidemiol.1994;8:301-13. | IV, DV
354 | Leventakou, V.,Roumeliotaki, T.,Koutra, K.,Vassilaki, M.,Mantzouranis, E.,Bitsios, P.,Kogevinas, M.,Chatzi, L. Breastfeeding duration and cognitive, language and motor development at 18 months of age: Rhea mother-child cohort in Crete, Greece. J Epidemiol Community Health.2015;69:232-9. | IV
355 | Li, C.,Kaur, H.,Choi, W. S.,Huang, T. T.,Lee, R. E.,Ahluwalia, J. S. Additive interactions of maternal prepregnancy BMI and breast-feeding on childhood overweight. Obes Res.2005;13:362-71. | IV
356 | Li, R.,Magadia, J.,Fein, S. B.,Grummer-Strawn, L. M. Risk of bottle-feeding for rapid weight gain during the first year of life. Arch Pediatr Adolesc Med.2012;166:431-6. | IV
357 | Lin, S. L.,Leung, G. M.,Lam, T. H.,Schooling, C. M. Timing of solid food introduction and obesity: Hong Kong’s “children of 1997” birth cohort. Pediatrics.2013;131:e1459-67. | Design
358 | Lind,T.,Lonnerdal,B.,Persson,L. A.,Stenlund,H.,Tennefors,C.,Hernell,O. Effects of weaning cereals with different phytate contents on hemoglobin, iron stores, and serum zinc: a randomized intervention in infants from 6 to 12 mo of age. Am J Clin Nutr.2003;78:168-75. | DV
359 | Livingstone V. Failure to thrive while breastfeeding. Breastfeed Med.2006;1:108-11. | Design
360 | Lozoff, B.,De Andraca, I.,Castillo, M.,Smith, J. B.,Walter, T.,Pino, P. Behavioral and developmental effects of preventing iron-deficiency anemia in healthy full-term infants. Pediatrics.2003;112:846-54. | IV
361 | Lucas, R.,Judge, M.,Sajdlowska, J.,Cong, X.,McGrath, J. M.,Brandon, D. Effect of Maternal Body Mass Index on Infant Breastfeeding Behaviors and Exclusive Direct Breastfeeding. J Obstet Gynecol Neonatal Nurs.2015;44:772-83. | DV
362 | Lutter, C. K.,Mora, J. O.,Habicht, J. P.,Rasmussen, K. M.,Robson, D. S.,Herrera, M. G. Age-specific responsiveness of weight and length to nutritional supplementation. Am J Clin Nutr.1990;51:359-64. | IV
363 | Lutter, C. K.,Mora, J. O.,Habicht, J. P.,Rasmussen, K. M.,Robson, D. S.,Sellers, S. G.,Super, C. M.,Herrera, M. G. Nutritional supplementation: effects on child stunting because of diarrhea. Am J Clin Nutr.1989;50:1-8. | IV
364 | Lutter,C. K.,Rodriguez,A.,Fuenmayor,G.,Avila,L.,Sempertegui,F.,Escobar,J. Growth and micronutrient status in children receiving a fortified complementary food. J Nutr.2008;138:379-88. | IV
365 | Luukkainen,P.,Salo,M. K.,Visakorpi,J. K.,Raiha,N. C.,Nikkari,T. Impact of solid food on plasma arachidonic and docosahexaenoic acid status of term infants at 8 months of age. J Pediatr Gastroenterol Nutr.1996;23:229-34. | IV, DV
366 | MacCarthy, D. Psychological influences affecting growth. Health Visit.1980;53:470-6. | Design
367 | Magarey, A.,Kavian, F.,Scott, J. A.,Markow, K.,Daniels, L. Feeding Mode of Australian Infants in the First 12 Months of Life: An Assessment against National Breastfeeding Indicators. J Hum Lact.2015. | DV
368 | Maimaitiming, T.,Wang, Y. P. Feeding and intellectual development in infants and children from Uygur, Kazak, and Han nationality: A comparison of 454 cases. Journal of Clinical Rehabilitative Tissue Engineering Research.2007;11:10710-10712. | Design
369 | Makrides,M.,Gould,J. F.,Gawlik,N. R.,Yelland,L. N.,Smithers,L. G.,Anderson,P. J.,Gibson,R. A. Four-year follow-up of children born to women in a randomized trial of prenatal DHA supplementation. Jama.2014;311:1802-4. | IV
370 | Male,C.,Persson,L. A.,Freeman,V.,Guerra,A.,van’t Hof,M. A.,Haschke,F. Prevalence of iron deficiency in 12-mo-old infants from 11 European areas and influence of dietary factors on iron status (Euro-Growth study). Acta Paediatr.2001;90:492-8. | DV
371 | Mallan, K. M.,Fildes, A.,Magarey, A. M.,Daniels, L. A. The Relationship between Number of Fruits, Vegetables, and Noncore Foods Tried at Age 14 Months and Food Preferences, Dietary Intake Patterns, Fussy Eating Behavior, and Weight Status at Age 3.7 Years. J Acad Nutr Diet.2016;116:630-7. | DV
372 | Mallard,S. R.,Houghton,L. A.,Filteau,S.,Mullen,A.,Nieuwelink,J.,Chisenga,M.,Siame,J.,Gibson,R. S. Dietary diversity at 6 months of age is associated with subsequent growth and mediates the effect of maternal education on infant growth in urban Zambia. J Nutr.2014;144:1818-25. | Country
373 | Mamabolo, R. L.,Alberts, M.,Mbenyane, G. X.,Steyn, N. P.,Nthangeni, N. G.,Delemarre-Van De Waal, H. A.,Levitt, N. S. Feeding practices and growth of infants from birth to 12 months in the central region of the Limpopo Province of South Africa. Nutrition.2004;20:327-33. | IV, DV
374 | Mamabolo,R. L.,Alberts,M.,Levitt,N. S.,Delemarre-van de Waal,H. A.,Steyn,N. P. Association between insulin-like growth factor-1, insulin-like growth factor-binding protein-1 and leptin levels with nutritional status in 1-3-year-old children, residing in the central region of Limpopo Province, South Africa. Br J Nutr.2007;98:762-9. | IV
375 | Mamun, A. A.,Lawlor, D. A.,O’Callaghan, M. J.,Williams, G. M.,Najman, J. M. Family and early life factors associated with changes in overweight status between ages 5 and 14 years: findings from the Mater University Study of Pregnancy and its outcomes. Int J Obes (Lond).2005;29:475-82. | IV
376 | Manjrekar, C.,Vishalakshi, M. P.,Begum, N. J.,Padma, G. N. Breast feeding ability of undernourished mothers and physical development of their infants during 0-1 year. Indian Pediatr.1985;22:801-9. | IV, DV
377 | Marques,R. C.,Dorea,J. G.,Bernardi,J. V.,Bastos,W. R.,Malm,O. Maternal fish consumption in the nutrition transition of the Amazon Basin: growth of exclusively breastfed infants during the first 5 years. Ann Hum Biol.2008;35:363-77. | IV
378 | Marquis, G. S.,Habicht, J. P.,Lanata, C. F.,Black, R. E.,Rasmussen, K. M. Association of breastfeeding and stunting in Peruvian toddlers: an example of reverse causality. Int J Epidemiol.1997;26:349-56. | Design
379 | Marquis, G. S.,Habicht, J. P.,Lanata, C. F.,Black, R. E.,Rasmussen, K. M. Breast milk or animal-product foods improve linear growth of Peruvian toddlers consuming marginal diets. Am J Clin Nutr.1997;66:1102-9. | Design
380 | Martin, R. M.,McCarthy, A.,Smith, G. D.,Davies, D. P.,Ben-Shlomo, Y. Infant nutrition and blood pressure in early adulthood: the Barry Caerphilly Growth study. Am J Clin Nutr.2003;77:1489-97. | IV, DV
381 | Martin, R. M.,Smith, G. D.,Mangtani, P.,Frankel, S.,Gunnell, D. Association between breast feeding and growth: the Boyd-Orr cohort study. Arch Dis Child Fetal Neonatal Ed.2002;87:F193-201. | IV
382 | Martines, J. C.,Habicht, J. P.,Ashworth, A.,Kirkwood, B. R. Weaning in southern Brazil: is there a “weanling’s dilemma”?. J Nutr.1994;124:1189-98. | IV
383 | Matsuzaki,M.,Kuper,H.,Kulkarni,B.,Radhakrishna,K. V.,Viljakainen,H.,Taylor,A. E.,Sullivan,R.,Bowen,L.,Tobias,J. H.,Ploubidis,G. B.,Wells,J. C.,Prabhakaran,D.,Smith,G. D.,Ebrahim,S.,Ben-Shlomo,Y.,Kinra,S. Life-course determinants of bone mass in young adults from a transitional rural community in India: The Andhra Pradesh Children and Parents Study (APCAPS). American Journal of Clinical Nutrition.2014;99:1450-1459. | Design, IV, Age
384 | May, A. L.,Dietz, W. H. The Feeding Infants and Toddlers Study 2008: opportunities to assess parental, cultural, and environmental influences on dietary behaviors and obesity prevention among young children. J Am Diet Assoc.2010;110:S11-5. | Design
385 | Mazariegos,M.,Hambidge,K. M.,Westcott,J. E.,Solomons,N. W.,Raboy,V.,Das,A.,Goco,N.,Kindem,M.,Wright,L. L.,Krebs,N. F. Neither a zinc supplement nor phytate-reduced maize nor their combination enhance growth of 6- to 12-month-old Guatemalan infants. J Nutr.2010;140:1041-8. | Country
386 | McGuire, E. Breastfeeding and high maternal body mass index. Breastfeed Rev.2013;21:7-14. | Design
387 | McNeill, G. Birth weight, feeding practices and weight-for-age of Punjabi children in the UK and in the rural Punjab. Hum Nutr Clin Nutr.1985;39:69-72. | Design
388 | Mehta KC,Specker BL,Bartholmey S,Giddens J,Ho ML. Trial on timing of introduction to solids and food type on infant growth. Pediatrics.1998;102:569-73. | IV
389 | Mei, H.,Guo, B.,Yin, B.,Liang, X.,Adair, L.,Thompson, A.,Zhang, J. Interactive Effects of Early Exclusive Breastfeeding and Pre-Pregnancy Maternal Weight Status on Young Children’s BMI - A Chinese Birth Cohort. PLoS One.2015;10:e0144357. | IV
390 | Meldrum,S. J.,D’Vaz,N.,Simmer,K.,Dunstan,J. A.,Hird,K.,Prescott,S. L. Effects of high-dose fish oil supplementation during early infancy on neurodevelopment and language: a randomised controlled trial. Br J Nutr.2012;108:1443-54. | IV
391 | Melnik, B. Growth and puberty in German children: is there still a positive secular trend? Consumption of milk as a vital factor in growth development..Bettina Gohlke, Woelfle JF. volume 23/2009. Deutsches Aerzteblatt International.2009;106:656-656. | Design
392 | Mennella, J. A.,Castor, S. M. Sensitive period in flavor learning: effects of duration of exposure to formula flavors on food likes during infancy. Clin Nutr.2012;31:1022-5. | DV
393 | Merten, S.,Dratva, J.,Ackermann-Liebrich, U. Do baby-friendly hospitals influence breastfeeding duration on a national level?. Pediatrics.2005;116:e702-8. | Design, IV
394 | Michaelsen, K. F.,Johansen, J. S.,Samuelson, G.,Price, P. A.,Christiansen, C. Serum bone gamma-carboxyglutamic acid protein in a longitudinal study of infants: lower values in formula-fed infants. Pediatr Res.1992;31:401-5. | IV
395 | Michaelsen, K. F. Are there negative effects of an excessive protein intake?. Pediatrics.2000;106:1293. | Design
396 | Michaelsen,K. F.,Milman,N.,Samuelson,G. A longitudinal study of iron status in healthy Danish infants: effects of early iron status, growth velocity and dietary factors. Acta Paediatr.1995;84:1035-44. | IV, DV
397 | Michaelsen,K. F. Cows’ milk in complementary feeding. Pediatrics.2000;106:1302-3. | Design
398 | Michaelsen,K. F. Nutrition and growth during infancy. The Copenhagen Cohort Study. Acta Paediatr Suppl.1997;420:1-36. | Design, IV
399 | Michels, K. B.,Willett, W. C.,Graubard, B. I.,Vaidya, R. L.,Cantwell, M. M.,Sansbury, L. B.,Forman, M. R. A longitudinal study of infant feeding and obesity throughout life course. Int J Obes (Lond).2007;31:1078-85. | IV
400 | Mihrshahi, S.,Battistutta, D.,Magarey, A.,Daniels, L. A. Determinants of rapid weight gain during infancy: baseline results from the NOURISH randomised controlled trial. BMC Pediatr.2011;11:99. | Design
401 | Millar, L.,Kremer, P.,de Silva-Sanigorski, A.,McCabe, M. P.,Mavoa, H.,Moodie, M.,Utter, J.,Bell, C.,Malakellis, M.,Mathews, L.,Roberts, G.,Robertson, N.,Swinburn, B. A. Reduction in overweight and obesity from a 3-year community-based intervention in Australia: the ‘It’s Your Move!’ project. Obes Rev.2011;12 Suppl 2:20-8. | IV, Age
402 | Mimouni-Bloch, A.,Kachevanskaya, A.,Mimouni, F. B.,Shuper, A.,Raveh, E.,Linder, N. Breastfeeding may protect from developing attention-deficit/hyperactivity disorder. Breastfeed Med.2013;8:363-7. | IV
403 | Mittal, S.,Gupta, M. C. Evaluation of a supplementary feeding programme through take home system. J Trop Pediatr.1980;26:50-3. | IV
404 | Miura T,Fukuda M,Mizuno M,Ohte N. Need for public awareness regarding low birth weight and bottle feeding. Hypertens Res.2016. | Design
405 | Molgaard, C.,Larnkjaer, A.,Mark, A. B.,Michaelsen, K. F. Are early growth and nutrition related to bone health in adolescence? The Copenhagen Cohort Study of infant nutrition and growth. Am J Clin Nutr.2011;94:1865s-1869s. | IV
406 | Moller, L. M.,de Hoog, M. L.,van Eijsden, M.,Gemke, R. J.,Vrijkotte, T. G. Infant nutrition in relation to eating behaviour and fruit and vegetable intake at age 5 years. Br J Nutr.2013;109:564-71. | DV
407 | Monterrosa EC,Frongillo EA,Neufeld LM,Egan KA,Ramakrishnan U,Rasmussen KM. Maternal pre-pregnancy body mass index is not associated with infant and young child feeding in low-income Mexican children 1-24 months old. Matern Child Nutr.2015;11:215-28. | DV
408 | Monterrosa,E. C.,Frongillo,E. A.,Vasquez-Garibay,E. M.,Romero-Velarde,E.,Casey,L. M.,Willows,N. D. Predominant breast-feeding from birth to six months is associated with fewer gastrointestinal infections and increased risk for iron deficiency among infants. J Nutr.2008;138:1499-504. | IV
409 | Monti G,Viola S,Baro C,Cresi F,Tovo PA,Moro G,Ferrero MP,Conti A,Bertino E. Tolerability of donkey’s milk in 92 highly-problematic cow’s milk allergic children. J Biol Regul Homeost Agents.2012;26:75-82. | IV
410 | Moore,S. E.,Prentice,A. M.,Wagatsuma,Y.,Fulford,A. J.,Collinson,A. C.,Raqib,R.,Vahter,M.,Persson,L. A.,Arifeen,S. E. Early-life nutritional and environmental determinants of thymic size in infants born in rural Bangladesh. Acta Paediatr.2009;98:1168-75. | IV, DV
411 | Moreno M. Early infant feeding and obesity risk. JAMA Pediatr.2014;168:1084. | Design
412 | Morgan JB,Mumford PM. A follow-up study of nutrition and anthropometry in pre-school children. Proc Nutr Soc.1980;39:5a. | Design
413 | Morgan, J. B.,Lucas, A.,Fewtrell, M. S. Does weaning influence growth and health up to 18 months?. Archives of Disease in Childhood: Education and Practice Edition.2004;89:728-733. | Design
414 | Morley,R.,Abbott,R.,Fairweather-Tait,S.,MacFadyen,U.,Stephenson,T.,Lucas,A. Iron fortified follow on formula from 9 to 18 months improves iron status but not development or growth: a randomised trial. Arch Dis Child.1999;81:247-52. | IV
415 | Morrow-Tlucak, M.,Haude, R. H.,Ernhart, C. B. Breastfeeding and cognitive development in the first 2 years of life. Soc Sci Med.1988;26:635-9. | IV
416 | Morton,R. E.,Nysenbaum,A.,Price,K. Iron status in the first year of life. J Pediatr Gastroenterol Nutr.1988;7:707-12. | DV
417 | Mumford, P.,Morgan, J. B. A longitudinal study of nutrition and growth of infants initially on the upper and lower centile for weight and age. Int J Obes.1982;6:335-41. | IV, DV
418 | Musaad, S. M.,Donovan, S. M.,Fiese, B. H. Parental perception of child weight in the first two years-of-life: a potential link between infant feeding and preschoolers’ diet. Appetite.2015;91:90-100. | Design, DV
419 | Nagahara, K.,Dobashi, K.,Itabashi, K. Feeding choice has a gender-associated effect on infant growth. Pediatr Int.2013;55:481-7. | IV
420 | Nakao, R. M. Effects of an education program on the health and illness profile of rural breast-fed babies. Philipp J Nurs.1988;58:12-8. | IV
421 | Narese, F.,Puccio, G.,Mazzucco, W.,Falzone, A.,Venturella, V.,Narese, D.,Capra, E. Earlier appearance of the ossification center of the femoral head in breast-fed versus formula-fed infants. Nutrition.2011;27:1108-11. | Design, IV
422 | Nauta,A. J.,Garssen,J. Nutritional programming of immune defense against infections in early life. Nutricia Research, Utrecht, Netherlands.2014;12:113-126. | Design
423 | Newman,J. E.,Garces,A.,Mazariegos,M.,Michael Hambidge,K.,Manasyan,A.,Tshefu,A.,Lokangaka,A.,Sami,N.,Carlo,W. A.,Bose,C. L.,Pasha,O.,Goco,N.,Chomba,E.,Goldenberg,R. L.,Wright,L. L.,Koso-Thomas,M.,Krebs,N. F. Theory-driven process evaluation of a complementary feeding trial in four countries. Health Educ Res.2014;29:297-305. | Design, DV
424 | Ng, S. C.,Chong, Y. S.,Rauff, M.,Myo, Z. M.,Nurfarah, C.,Deurenberg, P. R. The influence of breast feeding compared to formula feeding on infant adiposity. Ann Acad Med Singapore.2004;33:S75. | Design, IV
425 | Nguyen, N. D.,Allen, J. R.,Peat, J. K.,Schofield, W. N.,Nossar, V.,Eisenbruch, M.,Gaskin, K. J. Growth and feeding practices of Vietnamese infants in Australia. Eur J Clin Nutr.2004;58:356-62. | IV, DV
426 | Nielsen GA,Thomsen BL,Michaelsen KF. Influence of breastfeeding and complementary food on growth between 5 and 10 months. Acta Paediatr.1998;87:911-7. | Design
427 | Niinikoski, H.,Lagstrom, H.,Jokinen, E.,Siltala, M.,Ronnemaa, T.,Viikari, J.,Raitakari, O. T.,Jula, A.,Marniemi, J.,Nanto-Salonen, K.,Simell, O. Impact of repeated dietary counseling between infancy and 14 years of age on dietary intakes and serum lipids and lipoproteins: the STRIP study. Circulation.2007;116:1032-40. | IV
428 | Northstone, K.,Emmett, P.,Nethersole, F. The effect of age of introduction to lumpy solids on foods eaten and reported feeding difficulties at 6 and 15 months. J Hum Nutr Diet.2001;14:43-54. | DV
429 | Novotny, R.,Coleman, P.,Tenorio, L.,Davison, N.,Camacho, T.,Ramirez, V.,Vijayadeva, V.,Untalan, P.,Tudela, M. D. Breastfeeding is associated with lower body mass index among children of the Commonwealth of the Northern Mariana Islands. J Am Diet Assoc.2007;107:1743-6. | Design, IV
430 | Ntouva, A.,Rogers, I.,MacAdam, A.,Emmett, P. Weaning practices and iron status of exclusively breast fed infants. Journal of Human Nutrition & Dietetics.2011;24:297-298 2p. | Design
431 | Nwaru BI,Takkinen HM,Niemela O,Kaila M,Erkkola M,Ahonen S,Haapala AM,Kenward MG,Pekkanen J,Lahesmaa R,Kere J,Simell O,Veijola R,Ilonen J,Hyoty H,Knip M,Virtanen SM. Timing of infant feeding in relation to childhood asthma and allergic diseases. J Allergy Clin Immunol.2013;131:78-86. | DV
432 | Obatolu, V. A. Growth pattern of infants fed with a mixture of extruded malted maize and cowpea. Nutrition.2003;19:174-8. | Country
433 | Oddy, W. H.,Kendall, G. E.,Blair, E.,De Klerk, N. H.,Stanley, F. J.,Landau, L. I.,Silburn, S.,Zubrick, S. Breast feeding and cognitive development in childhood: a prospective birth cohort study. Paediatr Perinat Epidemiol.2003;17:81-90. | IV
434 | Oddy, W. H.,Robinson, M.,Kendall, G. E.,Li, J.,Zubrick, S. R.,Stanley, F. J. Breastfeeding and early child development: a prospective cohort study. Acta Paediatr.2011;100:992-9. | IV
435 | Oddy, W. H.,Sherriff, J. L. Breastfeeding, body mass index, asthma and atopy in children. Asia Pac J Public Health.2003;15 Suppl:S15-7. | IV
436 | O’Donovan,S. M.,O’B Hourihane J,Murray,D. M.,Kenny,L. C.,Khashan,A. S.,Chaoimh,C. N.,Irvine,A. D.,Kiely,M. Neonatal adiposity increases the risk of atopic dermatitis during the first year of life. J Allergy Clin Immunol.2015. | DV
437 | Oelofse,A.,Van Raaij,J. M.,Benade,A. J.,Dhansay,M. A.,Tolboom,J. J.,Hautvast,J. G. The effect of a micronutrient-fortified complementary food on micronutrient status, growth and development of 6- to 12-month-old disadvantaged urban South African infants. Int J Food Sci Nutr.2003;54:399-407. | Country
438 | Ong, K. K.,Emmett, P. M.,Noble, S.,Ness, A.,Dunger, D. B. Dietary energy intake at the age of 4 months predicts postnatal weight gain and childhood body mass index. Pediatrics.2006;117:e503-8. | IV
439 | Ong, K. K.,Preece, M. A.,Emmett, P. M.,Ahmed, M. L.,Dunger, D. B. Size at birth and early childhood growth in relation to maternal smoking, parity and infant breast-feeding: longitudinal birth cohort study and analysis. Pediatr Res.2002;52:863-7. | IV
440 | Onyango, A. W.,Borghi, E.,de Onis, M.,Casanovas Mdel, C.,Garza, C. Complementary feeding and attained linear growth among 6-23-month-old children. Public Health Nutr.2014;17:1975-83. | Design
441 | Ou, X.,Andres, A.,Cleves, M. A.,Pivik, R. T.,Snow, J. H.,Ding, Z.,Badger, T. M. Sex-specific association between infant diet and white matter integrity in 8-y-old children. Pediatr Res.2014;76:535-43. | IV
442 | Ounsted, M. K.,Moar, V. A.,Scott, A. Large-for-dates babies at the age of four years: health, handicap and developmental status. Early Hum Dev.1983;9:9-19. | IV
443 | Pachucki MA. Food pattern analysis over time: unhealthful eating trajectories predict obesity. Int J Obes (Lond).2012;36:686-94. | Age
444 | Parry, J. E.,Ip, D. K.,Chau, P. Y.,Wu, K. M.,Tarrant, M. Predictors and consequences of in-hospital formula supplementation for healthy breastfeeding newborns. J Hum Lact.2013;29:527-36. | IV, DV
445 | Parsons, T. J.,Power, C.,Manor, O. Infant feeding and obesity through the lifecourse. Arch Dis Child.2003;88:793-4. | IV
446 | Patsourou, A.,Konstantinides, T.,Mantadakis, E.,Tsalkidis, A.,Zarras, C.,Balaska, A.,Simopoulos, K.,Chatzimichael, A. Growth of exclusively breastfed and self-weaned children of Greece aged 0-36 months. Breastfeed Med.2012;7:521-5. | IV
447 | Paul IM,Savage JS,Anzman SL,Beiler JS,Marini ME,Stokes JL,Birch LL. Preventing obesity during infancy: a pilot study. Obesity (Silver Spring).2011;19:353-61. | IV
448 | Paul, A.,Whitehead, R. Infant feeding: the weighting game. Community Outlook.1986:11-7. | Design
449 | Paul, S. P.,Smith, B. A.,Taylor, T. M.,Walker, J. Take with a grain of salt. Clin Chem.2013;59:348-51. | Design
450 | Peat,J. K.,Mihrshahi,S.,Kemp,A. S.,Marks,G. B.,Tovey,E. R.,Webb,K.,Mellis,C. M.,Leeder,S. R. Three-year outcomes of dietary fatty acid modification and house dust mite reduction in the Childhood Asthma Prevention Study. J Allergy Clin Immunol.2004;114:807-13. | IV, DV
451 | Penny,M. E.,Creed-Kanashiro,H. M.,Robert,R. C.,Narro,M. R.,Caulfield,L. E.,Black,R. E. Effectiveness of an educational intervention delivered through the health services to improve nutrition in young children: a cluster-randomised controlled trial. Lancet.2005;365:1863-72. | IV
452 | Penrod,J. C.,Anderson,K.,Acosta,P. B. Impact on iron status of introducing cow’s milk in the second six months of life. J Pediatr Gastroenterol Nutr.1990;10:462-7. | IV, DV
453 | Perez-Escamilla, R.,Cohen, R. J.,Brown, K. H.,Rivera, L. L.,Canahuati, J.,Dewey, K. G. Maternal anthropometric status and lactation performance in a low-income Honduran population: evidence for the role of infants. Am J Clin Nutr.1995;61:528-34. | IV, DV
454 | Persson LA. Infant feeding and growth--a longitudinal study in three Swedish communities. Ann Hum Biol.1985;12:41-52. | IV
455 | Persson,L. A.,Lundstrom,M.,Lonnerdal,B.,Hernell,O. Are weaning foods causing impaired iron and zinc status in 1-year-old Swedish infants? A cohort study. Acta Paediatr.1998;87:618-22. | IV, DV
456 | Peters,R. L.,Allen,K. J.,Dharmage,S. C.,Lodge,C. J.,Koplin,J. J.,Ponsonby,A. L.,Wake,M.,Lowe,A. J.,Tang,M. L.,Matheson,M. C.,Gurrin,L. C. Differential factors associated with challenge-proven food allergy phenotypes in a population cohort of infants: a latent class analysis. Clin Exp Allergy.2015;45:953-63. | DV
457 | Pfluger M,Winkler C,Hummel S,Ziegler AG. Early infant diet in children at high risk for type 1 diabetes. Horm Metab Res.2010;42:143-8. | IV
458 | Pham,V. P.,Nguyen,V. H.,Salvignol,B.,Treche,S.,Wieringa,F. T.,Dijkhuizen,M. A.,Nguyen,C. K.,Pham,D. T.,Schwartz,H.,Berger,J. A six-month intervention with two different types of micronutrient-fortified complementary foods had distinct short- and long-term effects on linear and ponderal growth of Vietnamese infants. J Nutr.2012;142:1735-40. | Country
459 | Phu,P. V.,Hoan,N. V.,Salvignol,B.,Treche,S.,Wieringa,F. T.,Khan,N. C.,Tuong,P. D.,Berger,J. Complementary foods fortified with micronutrients prevent iron deficiency and anemia in Vietnamese infants. J Nutr.2010;140:2241-7. | DV
460 | Piemontese, P.,Gianni, M. L.,Braegger, C. P.,Chirico, G.,Gruber, C.,Riedler, J.,Arslanoglu, S.,van Stuijvenberg, M.,Boehm, G.,Jelinek, J.,Roggero, P. Tolerance and safety evaluation in a large cohort of healthy infants fed an innovative prebiotic formula: a randomized controlled trial. PLoS One.2011;6:e28010. | IV
461 | Pimpin, L.,Jebb, S.,Johnson, L.,Wardle, J.,Ambrosini, G. L. Dietary protein intake is associated with body mass index and weight up to 5 y of age in a prospective cohort of twins. Am J Clin Nutr.2016;103:389-97. | IV
462 | Pivik, R. T.,Andres, A.,Badger, T. M. Effects of diet on early stage cortical perception and discrimination of syllables differing in voice-onset time: a longitudinal ERP study in 3 and 6 month old infants. Brain Lang.2012;120:27-41. | IV
463 | Pivik, R. T.,Dykman, R. A.,Jing, H.,Gilchrist, J. M.,Badger, T. M. The influence of infant diet on early developmental changes in processing human voice speech stimuli: ERP variations in breast and milk formula-fed infants at 3 and 6 months after birth. Dev Neuropsychol.2007;31:279-335. | IV
464 | Piwoz, E. G.,Black, R. E.,Lopez de Romana, G.,Creed de Kanashiro, H.,Brown, K. H. The relationship between infants’ preceding appetite, illness, and growth performance and mothers’ subsequent feeding practice decisions. Soc Sci Med.1994;39:851-60. | IV, DV
465 | Piwoz, E. G.,Creed de Kanashiro, H.,Lopez de Romana, G.,Black, R. E.,Brown, K. H. Within- and between-individual variation in energy intakes by low-income Peruvian infants. Eur J Clin Nutr.1994;48:333-40. | IV, DV
466 | Piwoz,E. G.,Lopez de Romana,G.,Creed de Kanashiro,H.,Black,R. E.,Brown,K. H. Indicators for monitoring the growth of peruvian infants: weight and length gain vs attained weight and length. Am J Public Health.1994;84:1132-8. | IV
467 | Plagemann, A.,Harder, T.,Kohlhoff, R.,Fahrenkrog, S.,Rodekamp, E.,Franke, K.,Dudenhausen, J. W. Impact of early neonatal breast-feeding on psychomotor and neuropsychological development in children of diabetic mothers. Diabetes Care.2005;28:573-8. | IV
468 | Plonka, K. A.,Pukallus, M. L.,Barnett, A.,Holcombe, T. F.,Walsh, L. J.,Seow, W. K. A controlled, longitudinal study of home visits compared to telephone contacts to prevent early childhood caries. Int J Paediatr Dent.2013;23:23-31. | DV
469 | Poh,Bee Koon,Ng,Boon Koon,Siti Haslinda,Mohd Din,Nik Shanita,Safii,Wong,Jyh Eiin,Budin,Siti Balkis,Ruzita,Abd Talib,Ng,Lai Oon,Khouw,Ilse,Norimah,A. Karim. Nutritional status and dietary intakes of children aged 6 months to 12 years: findings of the Nutrition Survey of Malaysian Children (SEANUTS Malaysia). British Journal of Nutrition.2013;110:S21-35 1p. | Design, IV
470 | Polańska, K.,Muszyński, P.,Sobala, W.,Dziewirska, E.,Merecz-Kot, D.,Hanke, W. Maternal lifestyle during pregnancy and child psychomotor development - Polish Mother and Child Cohort study. Early Human Development.2015;91:317-325. | IV
471 | Pollitt, E.,Gorman, K. S.,Engle, P. L.,Rivera, J. A.,Martorell, R. Nutrition in early life and the fulfillment of intellectual potential. J Nutr.1995;125:1111s-1118s. | Design, IV
472 | Pollitt, E.,Watkins, W. E.,Husaini, M. A. Three-month nutritional supplementation in Indonesian infants and toddlers benefits memory function 8 y later. Am J Clin Nutr.1997;66:1357-63. | Country
473 | Potur, A. H.,Kalmaz, N. An investigation into feeding errors of 0-4-month-old infants. J Trop Pediatr.1995;41:120-2. | Design, IV, DV
474 | Potur, A. H.,Kalmaz, N. An investigation into feeding errors of 0-4-month-old infants. J Trop Pediatr.1996;42:173-5. | Design, IV, DV
475 | Prentice P,Koulman A,Matthews L,Acerini CL,Ong KK,Dunger DB. Lipidomic analyses, breast- and formula-feeding, and growth in infants. J Pediatr.2015;166:276-81.e6. | IV
476 | Pridham, K. F. Infant feeding and anticipatory care: supporting the adaptation of parents to their new babies. Matern Child Nurs J.1981;10:111-26. | Design
477 | Priego, T.,Sanchez, J.,Pico, C.,Ahrens, W.,Bammann, K.,De Henauw, S.,Fraterman, A.,Iacoviello, L.,Lissner, L.,Molnar, D.,Moreno, L. A.,Siani, A.,Tornaritis, M.,Veidebaum, T.,Palou, A. Influence of breastfeeding on blood-cell transcript-based biomarkers of health in children. Pediatr Obes.2014;9:463-70. | IV
478 | Prodam, F.,Roccio, M.,Trovato, L.,Ricotti, R.,Moia, S.,Giglione, E.,Petri, A.,Walker, G. E.,Bellone, S.,Bona, G. Adiponectin oligomers are similarly distributed in adequate-for-gestational-age obese children irrespective of feeding in their first year. Pediatr Res.2015;77:808-13. | IV, DV
479 | Puri, R.,Chawla, P.,Sharma, M.,Pershad, D. Impact of an on-going supplementary feeding programme on the mental abilities of children. Indian J Pediatr.1984;51:653-7. | IV
480 | Purwestri, R. C.,Scherbaum, V.,Inayati, D. A.,Wirawan, N. N.,Suryantan, J.,Bloem, M. A.,Pangaribuan, R. V.,Stuetz, W.,Hoffmann, V.,Qaim, M.,Biesalski, H. K.,Bellows, A. C. Supplementary feeding with locally-produced Ready-to-Use Food (RUF) for mildly wasted children on Nias Island, Indonesia: comparison of daily and weekly program outcomes. Asia Pac J Clin Nutr.2012;21:374-9. | Health status, IV
481 | Qureshi, B.,Morgan, J. B.,Kimer, A. C.,Donaldson, D.,Dickerson, J. W. Feeding practices and birth weights of infants in Southall, Middlesex. J R Soc Health.1988;108:77-80. | IV, DV
482 | Radhakrishna,K. V.,Hemalatha,R.,Geddam,J. J.,Kumar,P. A.,Balakrishna,N.,Shatrugna,V. Effectiveness of zinc supplementation to full term normal infants: a community based double blind, randomized, controlled, clinical trial. PLoS One.2013;8:e61486. | IV
483 | Ramokolo, V.,Lombard, C.,Chhagan, M.,Engebretsen, I. M.,Doherty, T.,Goga, A. E.,Fadnes, L. T.,Zembe, W.,Jackson, D. J.,Van den Broeck, J. Effects of early feeding on growth velocity and overweight/obesity in a cohort of HIV unexposed South African infants and children. Int Breastfeed J.2015;10:14. | IV
484 | Rao,S.,Rajpathak,V. Breastfeeding and weaning practices in relation to nutritional status of infants. Indian Pediatr.1992;29:1533-9. | IV, DV
485 | Rapley, G. Talking about weaning. Community Pract.2011;84:40-1. | Design
486 | Rask-Nissila,L.,Jokinen,E.,Terho,P.,Tammi,A.,Hakanen,M.,Ronnemaa,T.,Viikari,J.,Seppanen,R.,Valimaki,I.,Helenius,H.,Simell,O. Effects of diet on the neurologic development of children at 5 years of age: the STRIP project. J Pediatr.2002;140:328-33. | IV
487 | Ravelli, A. C.,van der Meulen, J. H.,Osmond, C.,Barker, D. J.,Bleker, O. P. Infant feeding and adult glucose tolerance, lipid profile, blood pressure, and obesity. Arch Dis Child.2000;82:248-52. | IV
488 | Reifsnider, E. Reversing growth deficiency in children: the effect of a community-based intervention. J Pediatr Health Care.1998;12:305-12. | Health status, IV
489 | Requejo,A. M.,Navia,B.,Ortega,R. M.,Lopez-Sobaler,A. M.,Quintas,E.,Gaspar,M. J.,Osorio,O. The age at which meat is first included in the diet affects the incidence of iron deficiency and ferropenic anaemia in a group of pre-school children from Madrid. Int J Vitam Nutr Res.1999;69:127-31. | Design
490 | Richards, M.,Wadsworth, M.,Rahimi-Foroushani, A.,Hardy, R.,Kuh, D.,Paul, A. Infant nutrition and cognitive development in the first offspring of a national UK birth cohort. Dev Med Child Neurol.1998;40:163-7. | IV
491 | Rifas-Shiman SL,Sherry B,Scanlon K,Birch LL,Gillman MW,Taveras EM. Does maternal feeding restriction lead to childhood obesity in a prospective cohort study?. Arch Dis Child.2011;96:265-9. | IV
492 | Rios-Castillo, I.,Cerezo, S.,Corvalan, C.,Martinez, M.,Kain, J. Risk factors during the prenatal period and the first year of life associated with overweight in 7-year-old low-income Chilean children. Matern Child Nutr.2015;11:595-605. | Design
493 | Rivera,J. A.,Habicht,J. P. Effect of supplementary feeding on the prevention of mild-to-moderate wasting in conditions of endemic malnutrition in Guatemala. Bull World Health Organ.2002;80:926-32. | IV
494 | Roberts, D. W. Growth of breast fed and bottle fed infants. N Z Med J.1980;92:45-6. | IV
495 | Robinson, S. M.,Simmonds, S. J.,Jameson, K. A.,Syddall, H. E.,Dennison, E. M.,Cooper, C.,Sayer, A. A. Muscle strength in older community-dwelling men is related to type of milk feeding in infancy. J Gerontol A Biol Sci Med Sci.2012;67:990-6. | IV
496 | Robinson, S.,Ntani, G.,Simmonds, S.,Syddall, H.,Dennison, E.,Sayer, A. A.,Barker, D.,Cooper, C. Type of milk feeding in infancy and health behaviours in adult life: findings from the Hertfordshire Cohort Study. Br J Nutr.2013;109:1114-22. | IV, DV
497 | Rogan, W. J.,Gladen, B. C. Breast-feeding and cognitive development. Early Hum Dev.1993;31:181-93. | IV
498 | Rolland-Cachera,M. F.,Maillot,M.,Deheeger,M.,Souberbielle,J. C.,Peneau,S.,Hercberg,S. Association of nutrition in early life with body fat and serum leptin at adult age. Int J Obes (Lond).2013;37:1116-22. | IV
499 | Rosado,J. L.,Lopez,P.,Garcia,O. P.,Alatorre,J.,Alvarado,C. Effectiveness of the nutritional supplement used in the Mexican Oportunidades programme on growth, anaemia, morbidity and cognitive development in children aged 12-24 months. Public Health Nutr.2011;14:931-7. | IV
500 | Routi, T.,Ronnemaa, T.,Lapinleimu, H.,Salo, P.,Viikari, J.,Leino, A.,Valimaki, I.,Jokinen, E.,Simell, O. Effect of weaning on serum lipoprotein(a) concentration: the STRIP baby study. Pediatr Res.1995;38:522-7. | IV, DV
501 | Rowland, M. G. The “why” and “when” of introducing food to infants: growth in young breast-fed infants and some nutritional implications. Am J Clin Nutr.1985;41:459-63. | Design
502 | Roy, S. K.,Fuchs, G. J.,Mahmud, Z.,Ara, G.,Islam, S.,Shafique, S.,Akter, S. S.,Chakraborty, B. Intensive nutrition education with or without supplementary feeding improves the nutritional status of moderately-malnourished children in Bangladesh. J Health Popul Nutr.2005;23:320-30. | Health status
503 | Rudnicka, A. R.,Owen, C. G.,Richards, M.,Wadsworth, M. E.,Strachan, D. P. Effect of breastfeeding and sociodemographic factors on visual outcome in childhood and adolescence. Am J Clin Nutr.2008;87:1392-9. | IV
504 | Rudy,C. A. Vegetarian diets for children. Pediatr Nurs.1984;10:329-33. | Design
505 | Ruel, M. T.,Rivera, J.,Habicht, J. P.,Martorell, R. Differential response to early nutrition supplementation: long-term effects on height at adolescence. Int J Epidemiol.1995;24:404-12. | IV, Date
506 | Russell, C. G.,Taki, S.,Azadi, L.,Campbell, K. J.,Laws, R.,Elliott, R.,Denney-Wilson, E. A qualitative study of the infant feeding beliefs and behaviours of mothers with low educational attainment. BMC Pediatr.2016;16:69. | DV
507 | Ryan, A. S.,Gussler, J. D. Biocultural factors affecting infant feeding and growth. Med Anthropol.1985;9:93-5. | Design
508 | Rzehak, P.,Sausenthaler, S.,Koletzko, S.,Reinhardt, D.,von Berg, A.,Kramer, U.,Berdel, D.,Bollrath, C.,Grubl, A.,Bauer, C. P.,Wichmann, H. E.,Heinrich, J. Long-term effects of hydrolyzed protein infant formulas on growth--extended follow-up to 10 y of age: results from the German Infant Nutritional Intervention (GINI) study. Am J Clin Nutr.2011;94:1803s-1807s. | IV
509 | Saco-Pollitt, C.,Triana, N.,Harahap, H.,Husaini, M.,Jahari, A. B.,Pollitt, E. The eco-cultural context of the undernourished children in a study on the effects of early supplementary feeding in Indonesia. Eur J Clin Nutr.2000;54 Suppl 2:S11-5. | Design, Health status
510 | Sacrey, L. A.,Karl, J. M.,Whishaw, I. Q. Development of rotational movements, hand shaping, and accuracy in advance and withdrawal for the reach-to-eat movement in human infants aged 6-12 months. Infant Behav Dev.2012;35:543-60. | IV, DV
511 | Saha, K. K.,Frongillo, E. A.,Alam, D. S.,Arifeen, S. E.,Persson, L. A.,Rasmussen, K. M. Appropriate infant feeding practices result in better growth of infants and young children in rural Bangladesh. Am J Clin Nutr.2008;87:1852-9. | IV
512 | Samuel, T. M.,Thomas, T.,Bhat, S.,Kurpad, A. V. Are infants born in baby-friendly hospitals being exclusively breastfed until 6 months of age?. Eur J Clin Nutr.2012;66:459-65. | IV
513 | Saner G,Dagoglu T,Uzkan I,Neyzi O. Promotion of breastfeeding in the postpartum mother. Turk J Pediatr.1985;27:63-8. | IV
514 | Sanger, R. G.,Bystrom, E. B. Breast feeding: does it affect oral facial growth?. Dent Hyg (Chic).1982;56:44-7. | Design
515 | Santos, I. S.,Matijasevich, A.,Assuncao, M. C.,Valle, N. C.,Horta, B. L.,Goncalves, H. D.,Gigante, D. P.,Martines, J. C.,Pelto, G.,Victora, C. G. Promotion of Weight Gain in Early Childhood Does Not Increase Metabolic Risk in Adolescents: A 15-Year Follow-Up of a Cluster-Randomized Controlled Trial. J Nutr.2015;145:2749-55. | IV
516 | Santos,I.,Victora,C. G.,Martines,J.,Goncalves,H.,Gigante,D. P.,Valle,N. J.,Pelto,G. Nutrition counseling increases weight gain among Brazilian children. J Nutr.2001;131:2866-73. | IV
517 | Satter, Ma,Jabin, Sa,Abedin, N.,Mf, Mf,Parvin, R.,Dhali, M.,Amin, Mz. Development and Evaluation of Weaning Foods Using Locally Available Nutritious Fruits in Bangladesh. Malaysian Journal of Nutrition.2014;20:83-92. | Design, IV, DV
518 | Savino, F.,Maccario, S.,Cresi, F.,Grasso, G.,Oggero, R.,Silvestro, L.,Mussa, G. C. Bioimpedance vector analysis in breastfed and formula-fed infants in the first six months of life. Adv Exp Med Biol.2004;554:501-4. | Design, IV
519 | Savino, F.,Sorrenti, M.,Benetti, S.,Lupica, M. M.,Liguori, S. A.,Oggero, R. Resistin and leptin in breast milk and infants in early life. Early Hum Dev.2012;88:779-82. | Design, IV
520 | Sawley, L. Infant feeding. Nursing (Lond).1989;3:18-23. | Design
521 | Sazawal,S.,Dhingra,P.,Dhingra,U.,Gupta,S.,Iyengar,V.,Menon,V. P.,Sarkar,A.,Black,R. E. Compliance with home-based fortification strategies for delivery of iron and zinc: its effect on haematological and growth markers among 6-24 months old children in north India. J Health Popul Nutr.2014;32:217-26. | Country
522 | Scaglioni, S.,Agostoni, C.,Notaris, R. D.,Radaelli, G.,Radice, N.,Valenti, M.,Giovannini, M.,Riva, E. Early macronutrient intake and overweight at five years of age. Int J Obes Relat Metab Disord.2000;24:777-81. | IV
523 | Scheiwe, A.,Hardy, R.,Watt, R. G. Four-year follow-up of a randomized controlled trial of a social support intervention on infant feeding practices. Matern Child Nutr.2010;6:328-37. | IV
524 | Schmalz, M.,Boos, K.,Schmalz, G.,Huntington, M. K. Failure to thrive. J Fam Pract.2009;58:539-44. | Design
525 | Schmidt,M. K.,Muslimatun,S.,West,C. E.,Schultink,W.,Gross,R.,Hautvast,J. G. Nutritional status and linear growth of Indonesian infants in west java are determined more by prenatal environment than by postnatal factors. J Nutr.2002;132:2202-7. | Country
526 | Schroeder, D. G.,Martorell, R.,Rivera, J. A.,Ruel, M. T.,Habicht, J. P. Age differences in the impact of nutritional supplementation on growth. J Nutr.1995;125:1051s-1059s. | IV
527 | Schroeder, N.,Rushovich, B.,Bartlett, E.,Sharma, S.,Gittelsohn, J.,Caballero, B. Early Obesity Prevention: A Randomized Trial of a Practice-Based Intervention in 0-24-Month Infants. J Obes.2015;2015:795859. | IV
528 | Schwartz, R.,Vigo, A.,de Oliveira, L. D.,Justo Giugliani, E. R. The Effect of a Pro-Breastfeeding and Healthy Complementary Feeding Intervention Targeting Adolescent Mothers and Grandmothers on Growth and Prevalence of Overweight of Preschool Children. PLoS One.2015;10:e0131884. | IV
529 | Scott, J. A.,Binns, C. W.,Graham, K. I.,Oddy, W. H. Predictors of the early introduction of solid foods in infants: results of a cohort study. BMC Pediatr.2009;9:60. | DV
530 | Scott, J. A.,Dashti, M.,Al-Sughayer, M.,Edwards, C. A. Timing and Determinants of the Introduction of Complementary Foods in Kuwait: Results of a Prospective Cohort Study. J Hum Lact.2015;31:467-73. | DV
531 | Scully, T. Obesity. Nature.2014;508:S49. | Design
532 | Seal, N.,Broome, M. E. Prepregnancy Body Mass Index and Feeding Practices in Relation to Infants’ Growth. J Nurse Pract.2013;9. | Design
533 | Seksaria,S. A.,Sheth,M. K. Mass media as a means to bring about behavioral changes in infant and young child feeding practices amongst tribal mothers of Chikhli taluka, Gujarat. Indian Journal of Public Health Research and Development.2015;6:113-118. | Design, IV
534 | Sellen, D. W.,Thompson, A. L.,Hruschka, D. J.,Stein, A. D.,Martorell, R. Early determinants of non-exclusive breastfeeding among Guatemalan infants. Adv Exp Med Biol.2004;554:299-301. | IV, DV
535 | Senarath, U.,Godakandage, S. S.,Jayawickrama, H.,Siriwardena, I.,Dibley, M. J. Determinants of inappropriate complementary feeding practices in young children in Sri Lanka: secondary data analysis of Demographic and Health Survey 2006-2007. Matern Child Nutr.2012;8 Suppl 1:60-77. | Design, DV
536 | Sethi, V.,Kashyap, S.,Seth, V. Effect of nutrition education of mothers on infant feeding practices. Indian J Pediatr.2003;70:463-6. | IV
537 | Sezer,R. G.,Aydemir,G.,Akcan,A. B.,Bayoglu,D. S.,Guran,T.,Bozaykut,A. Effect of breastfeeding on serum zinc levels and growth in healthy infants. Breastfeed Med.2013;8:159-63. | Design
538 | Shaternikov,V. A.,Fateeva,E. M.,Chernikov,M. N. Protein nutrition in early infancy and subsequent periods: its effect on further development. Bibl Nutr Dieta.1982:95-111. | Design
539 | Shehadeh, N.,Weitzer-Kish, H.,Shamir, R.,Shihab, S.,Weiss, R. Impact of early postnatal weight gain and feeding patterns on body mass index in adolescence. J Pediatr Endocrinol Metab.2008;21:9-15. | IV
540 | Shi,L.,Zhang,J.,Wang,Y.,Caulfield,L. E.,Guyer,B. Effectiveness of an educational intervention on complementary feeding practices and growth in rural China: a cluster randomised controlled trial. Public Health Nutr.2010;13:556-65. | IV
541 | Shim, J. E.,Kim, J.,Mathai, R. A. Associations of infant feeding practices and picky eating behaviors of preschool children. J Am Diet Assoc.2011;111:1363-8. | DV
542 | Simell, O.,Niinikoski, H.,Viikari, J.,Rask-Nissila, L.,Tammi, A.,Ronnemaa, T. Cardiovascular disease risk factors in young children in the STRIP baby project. Special Turku coronary Risk factor Intervention Project for children. Ann Med.1999;31 Suppl 1:55-61. | IV
543 | Simondon, K. B.,Gartner, A.,Berger, J.,Cornu, A.,Massamba, J. P.,San Miguel, J. L.,Ly, C.,Missotte, I.,Simondon, F.,Traissac, P.,Delpeuch, F.,Maire, B. Effect of early, short-term supplementation on weight and linear growth of 4-7-mo-old infants in developing countries: a four-country randomized trial. Am J Clin Nutr.1996;64:537-45. | IV, Country
544 | Singhal A,Cole TJ,Fewtrell M,Kennedy K,Stephenson T,Elias-Jones A,Lucas A. Promotion of faster weight gain in infants born small for gestational age: is there an adverse effect on later blood pressure?. Circulation.2007;115:213-20. | Health status, IV
545 | Singhal, A.,Lucas, A. Early origins of cardiovascular disease: is there a unifying hypothesis?. Lancet.2004;363:1642-5. | Design
546 | Skau,J. K.,Touch,B.,Chhoun,C.,Chea,M.,Unni,U. S.,Makurat,J.,Filteau,S.,Wieringa,F. T.,Dijkhuizen,M. A.,Ritz,C.,Wells,J. C.,Berger,J.,Friis,H.,Michaelsen,K. F.,Roos,N. Effects of animal source food and micronutrient fortification in complementary food products on body composition, iron status, and linear growth: a randomized trial in Cambodia. Am J Clin Nutr.2015;101:742-51. | IV
547 | Skledar, M. T.,Milosevic, M. Breastfeeding and time of complementary food introduction as predictors of obesity in children. Cent Eur J Public Health.2015;23:26-31. | Design
548 | Sloan, S.,Gildea, A.,Stewart, M.,Sneddon, H.,Iwaniec, D. Early weaning is related to weight and rate of weight gain in infancy. Child Care Health Dev.2008;34:59-64. | Design
549 | Snijders, B. E.,Thijs, C.,van Ree, R.,van den Brandt, P. A. Age at first introduction of cow milk products and other food products in relation to infant atopic manifestations in the first 2 years of life: the KOALA Birth Cohort Study. Pediatrics.2008;122:e115-22. | DV
550 | Soto-Ramirez, N.,Karmaus, W.,Zhang, H.,Davis, S.,Agarwal, S.,Albergottie, A. Modes of infant feeding and the occurrence of coughing/wheezing in the first year of life. J Hum Lact.2013;29:71-80. | IV, DV
551 | Sparks, J. W. Fetal growth and diet. Mead Johnson Symp Perinat Dev Med.1984:21-7. | Design
552 | Specker BL,Beck A,Kalkwarf H,Ho M. Randomized trial of varying mineral intake on total body bone mineral accretion during the first year of life. Pediatrics.1997;99:E12. | IV
553 | Spence,A. C.,Campbell,K. J.,Crawford,D. A.,McNaughton,S. A.,Hesketh,K. D. Mediators of improved child diet quality following a health promotion intervention: the Melbourne InFANT Program. Int J Behav Nutr Phys Act.2014;11:137. | IV, DV
554 | Sreedhara, M. S.,Banapurmath, C. R. A study of nutritional status of infants in relation to their complementary feeding practices. Current Pediatric Research.2014;18:39-41. | Design
555 | Stahl, M. D.,Guida, D. A. Slow weight gain in the breast-fed infant: management options. Pediatr Nurs.1984;10:117-20, 164. | Design
556 | Stang,J. Improving the eating patterns of infants and toddlers. J Am Diet Assoc.2006;106:S7-9. | Design
557 | Stifter, C. A.,Anzman-Frasca, S.,Birch, L. L.,Voegtline, K. Parent use of food to soothe infant/toddler distress and child weight status. An exploratory study. Appetite.2011;57:693-9. | Design, IV
558 | Strbak, V.,Skultetyova, M.,Hromadova, M.,Randuskova, A.,Macho, L. Late effects of breast-feeding and early weaning: seven-year prospective study in children. Endocr Regul.1991;25:53-7. | IV
559 | Stuff, J. E.,Garza, C.,Boutte, C.,Fraley, J. K.,Smith, E. O.,Klein, E. R.,Nichols, B. L. Sources of variance in milk and caloric intakes in breast-fed infants: implications for lactation study design and interpretation. Am J Clin Nutr.1986;43:361-6. | Design, IV
560 | Stuff, J. E.,Nichols, B. L. Nutrient intake and growth performance of older infants fed human milk. J Pediatr.1989;115:959-68. | DV
561 | Stunkard, A. J.,Berkowitz, R. I.,Schoeller, D.,Maislin, G.,Stallings, V. A. Predictors of body size in the first 2 y of life: a high-risk study of human obesity. Int J Obes Relat Metab Disord.2004;28:503-13. | IV
562 | Stunkard, A. J.,Berkowitz, R. I.,Stallings, V. A.,Schoeller, D. A. Energy intake, not energy output, is a determinant of body size in infants. Am J Clin Nutr.1999;69:524-30. | IV
563 | Super, C. M.,Herrera, M. G.,Mora, J. O. Long-term effects of food supplementation and psychosocial intervention on the physical growth of Colombian infants at risk of malnutrition. Child Dev.1990;61:29-49. | IV
564 | Svahn,J. C.,Feldl,F.,Raiha,N. C.,Koletzko,B.,Axelsson,I. E. Different quantities and quality of fat in milk products given to young children: effects on long chain polyunsaturated fatty acids and trans fatty acids in plasma. Acta Paediatr.2002;91:20-9. | DV
565 | Taitz, L. S.,Lukmanji, Z. Alterations in feeding patterns and rates of weight gain in South Yorkshire infants, 1971-1977. Hum Biol.1981;53:313-20. | IV, Date
566 | Taitz, L. Feeding children in the first year of life. Midwife Health Visitor & Community Nurse.1990;26:81-84. | Design
567 | Tann, S. P.,Wheeler, E. F. Food intakes and growth of young Chinese children in London. Community Med.1980;2:20-4. | IV, DV
568 | Tantracheewathorn,S.,Lohajaroensub,S. Incidence and risk factors of iron deficiency anemia in term infants. J Med Assoc Thai.2005;88:45-51. | IV, DV
569 | Tanzer F,Gumuser C. A study of the growth of 200 newborn babies for a period of 6 months according to the type of nutrition. Ann Trop Paediatr.1989;9:54-8. | IV
570 | Tarrant, M.,Fong, D. Y.,Wu, K. M.,Lee, I. L.,Wong, E. M.,Sham, A.,Lam, C.,Dodgson, J. E. Breastfeeding and weaning practices among Hong Kong mothers: a prospective study. BMC Pregnancy Childbirth.2010;10:27. | DV
571 | Taveras EM,Blackburn K,Gillman MW,Haines J,McDonald J,Price S,Oken E. First steps for mommy and me: a pilot intervention to improve nutrition and physical activity behaviors of postpartum mothers and their infants. Matern Child Health J.2011;15:1217-27. | IV
572 | Tawia, S. Breastfeeding, brain structure and function, cognitive development and educational attainment. Breastfeed Rev.2013;21:15-20. | Design
573 | Tawia, S. Childhood obesity and being breastfed. Breastfeed Rev.2013;21:42-8. | Design
574 | Taylor,A.,Redworth,E. W.,Morgan,J. B. Influence of diet on iron, copper, and zinc status in children under 24 months of age. Biol Trace Elem Res.2004;97:197-214. | DV
575 | Thakur, R.,Singh, M. G.,Chaudhary, S.,Manuja, N. Effect of mode of delivery and feeding practices on acquisition of oral Streptococcus mutans in infants. Int J Paediatr Dent.2012;22:197-202. | DV
576 | Theron, M.,Amissah, A.,Kleynhans, I. C.,Albertse, E.,MacIntyre, U. E. Inadequate dietary intake is not the cause of stunting amongst young children living in an informal settlement in Gauteng and rural Limpopo Province in South Africa: the NutriGro study. Public Health Nutr.2007;10:379-89. | Design
577 | Thomson, J. L.,Tussing-Humphreys, L. M.,Goodman, M. H. Delta Healthy Sprouts: a randomized comparative effectiveness trial to promote maternal weight control and reduce childhood obesity in the Mississippi Delta. Contemp Clin Trials.2014;38:82-91. | Design, IV
578 | Thorisdottir, B.,Gunnarsdottir, I.,Thorisdottir, A. V.,Palsson, G. I.,Halldorsson, T. I.,Thorsdottir, I. Nutrient intake in infancy and body mass index at six years in two population-based cohorts recruited before and after revision of infant dietary recommendations. Ann Nutr Metab.2013;63:145-51. | IV
579 | Thorsdottir, I.,Gunnarsdottir, I.,Palsson, G. I. Birth weight, growth and feeding in infancy: relation to serum lipid concentration in 12-month-old infants. Eur J Clin Nutr.2003;57:1479-85. | IV, DV
580 | Timby, N.,Domellof, E.,Hernell, O.,Lonnerdal, B.,Domellof, M. Neurodevelopment, nutrition, and growth until 12 mo of age in infants fed a low-energy, low-protein formula supplemented with bovine milk fat globule membranes: a randomized controlled trial. Am J Clin Nutr.2014;99:860-8. | IV
581 | Townsend, E.,Pitchford, N. J. Baby knows best? The impact of weaning style on food preferences and body mass index in early childhood in a case-controlled sample. BMJ Open.2012;2:e000298. | IV
582 | Tripathy, R.,Das, R. N.,Das, M. M.,Parija, A. C. Growth in the first year in children following IAP Policy on Infant Feeding. Indian Pediatr.2000;37:1051-9. | IV
583 | Tulldahl, J.,Pettersson, K.,Andersson, S. W.,Hulthen, L. Mode of infant feeding and achieved growth in adolescence: early feeding patterns in relation to growth and body composition in adolescence. Obes Res.1999;7:431-7. | Design
584 | Umer, A.,Hamilton, C.,Britton, C. M.,Mullett, M. D.,John, C.,Neal, W.,Lilly, C. L. Association between Breastfeeding and Childhood Obesity: Analysis of a Linked Longitudinal Study of Rural Appalachian Fifth-Grade Children. Child Obes.2015;11:449-55. | IV
585 | Unni, J. C.,Richard, J. Growth and morbidity of breast-fed and artificially-fed infants in urban south Indian families. J Trop Pediatr.1988;34:179-81. | IV
586 | Vail, B.,Prentice, P.,Dunger, D. B.,Hughes, I. A.,Acerini, C. L.,Ong, K. K. Age at Weaning and Infant Growth: Primary Analysis and Systematic Review. Journal of Pediatrics.2015;167:317-324.e1. | Design
587 | Valman, H. B. The first year of life: feeding and feeding problems. Br Med J.1980;280:457-60. | Design
588 | van der Willik, E. M.,Vrijkotte, T. G.,Altenburg, T. M.,Gademan, M. G.,Kist-van Holthe, J. Exclusively breastfed overweight infants are at the same risk of childhood overweight as formula fed overweight infants. Arch Dis Child.2015;100:932-7. | IV
589 | van Dijk, C. E.,Innis, S. M. Growth-curve standards and the assessment of early excess weight gain in infancy. Pediatrics.2009;123:102-8. | IV, DV
590 | van Eijsden, M.,Meijers, C. M.,Jansen, J. E.,de Kroon, M. L.,Vrijkotte, T. G. Cultural variation in early feeding pattern and maternal perceptions of infant growth. Br J Nutr.2015;114:481-8. | DV
591 | van Rheenen,P. F.,de Moor,L. T.,Eschbach,S.,Brabin,B. J. A cohort study of haemoglobin and zinc protoporphyrin levels in term Zambian infants: effects of iron stores at birth, complementary food and placental malaria. Eur J Clin Nutr.2008;62:1379-87. | Country
592 | van t Hof Msc, M. A. The influence of breastfeeding and complementary foods on growth until three years of age in the Euro-Growth Study. Pediatrics.2000;106:1281a-1281. | Design
593 | Vazir,S.,Engle,P.,Balakrishna,N.,Griffiths,P. L.,Johnson,S. L.,Creed-Kanashiro,H.,Fernandez Rao,S.,Shroff,M. R.,Bentley,M. E. Cluster-randomized trial on complementary and responsive feeding education to caregivers found improved dietary intake, growth and development among rural Indian toddlers. Matern Child Nutr.2013;9:99-117. | IV
594 | Veena SR,Krishnaveni GV,Srinivasan K,Wills AK,Hill JC,Kurpad AV,Muthayya S,Karat SC,Nalinakshi M,Fall CH. Infant feeding practice and childhood cognitive performance in South India. Arch Dis Child.2010;95:347-54. | Country
595 | Veena, S. R.,Krishnaveni, G. V.,Wills, A. K.,Hill, J. C.,Karat, S. C.,Fall, C. H. Glucose tolerance and insulin resistance in Indian children: relationship to infant feeding pattern. Diabetologia.2011;54:2533-7. | Country
596 | Vehapoglu, A.,Yazici, M.,Demir, A. D.,Turkmen, S.,Nursoy, M.,Ozkaya, E. Early infant feeding practice and childhood obesity: the relation of breast-feeding and timing of solid food introduction with childhood obesity. J Pediatr Endocrinol Metab.2014;27:1181-7. | Design
597 | Venancio, S. I.,Saldiva, S. R.,Mondini, L.,Levy, R. B.,Escuder, M. M. Early interruption of exclusive breastfeeding and associated factors, state of Sao Paulo, Brazil. J Hum Lact.2008;24:168-74. | Design, DV
598 | Verd S,Barriuso L,Gich I,Gutierrez A,Nadal-Amat J,Carreras E. Risk of early breastfeeding cessation among symmetrical, small for gestational age infants. Ann Hum Biol.2013;40:146-51. | Health status, DV
599 | Victora, C. G.,Matijasevich, A.,Santos, I. S.,Barros, A. J.,Horta, B. L.,Barros, F. C. Breastfeeding and feeding patterns in three birth cohorts in Southern Brazil: trends and differentials. Cad Saude Publica.2008;24 Suppl 3:S409-16. | IV, DV
600 | Victora,C. G.,Vaughan,J. P.,Martines,J. C.,Barcelos,L. B. Is prolonged breast-feeding associated with malnutrition?. Am J Clin Nutr.1984;39:307-14. | IV
601 | Villalpando, S. Feeding mode, infections, and anthropometric status in early childhood. Pediatrics.2000;106:1282-3. | Design
602 | Virtanen, S. M.,Laara, E.,Hypponen, E.,Reijonen, H.,Rasanen, L.,Aro, A.,Knip, M.,Ilonen, J.,Akerblom, H. K. Cow’s milk consumption, HLA-DQB1 genotype, and type 1 diabetes: a nested case-control study of siblings of children with diabetes. Childhood diabetes in Finland study group. Diabetes.2000;49:912-7. | DV
603 | Virtanen, S. M.,Rasanen, L.,Ylonen, K.,Aro, A.,Clayton, D.,Langholz, B.,Pitkaniemi, J.,Savilahti, E.,Lounamaa, R.,Tuomilehto, J.,et al.,. Early introduction of dairy products associated with increased risk of IDDM in Finnish children. The Childhood in Diabetes in Finland Study Group. Diabetes.1993;42:1786-90. | DV
604 | Vobecky,J. S.,Vobecky,J.,Shapcott,D.,Demers,P. P. Nutrient intake patterns and nutritional status with regard to relative weight in early infancy. Am J Clin Nutr.1983;38:730-8. | IV
605 | Wandel, M.,Fagerli, R. Aa,Olsen, P. T.,Borch-Iohnsen, B.,Ek, J. Iron status and weaning practices among Norwegian and immigrant infants. Nutrition Research.1996;16:251-265. | Design
606 | Wang RJ,Trehan I,LaGrone LN,Weisz AJ,Thakwalakwa CM,Maleta KM,Manary MJ. Investigation of food acceptability and feeding practices for lipid nutrient supplements and blended flours used to treat moderate malnutrition. J Nutr Educ Behav.2013;45:258-63. | Health status, Country
607 | Watt, R. G.,Tull, K. I.,Hardy, R.,Wiggins, M.,Kelly, Y.,Molloy, B.,Dowler, E.,Apps, J.,McGlone, P. Effectiveness of a social support intervention on infant feeding practices: randomised controlled trial. J Epidemiol Community Health.2009;63:156-62. | IV, DV
608 | Weber, M.,Grote, V.,Closa-Monasterolo, R.,Escribano, J.,Langhendries, J. P.,Dain, E.,Giovannini, M.,Verduci, E.,Gruszfeld, D.,Socha, P.,Koletzko, B. Lower protein content in infant formula reduces BMI and obesity risk at school age: follow-up of a randomized trial. Am J Clin Nutr.2014;99:1041-51. | IV
609 | Weijs, P. J.,Kool, L. M.,van Baar, N. M.,van der Zee, S. C. High beverage sugar as well as high animal protein intake at infancy may increase overweight risk at 8 years: a prospective longitudinal pilot study. Nutr J.2011;10:95. | IV
610 | Wen, L. M.,Baur, L. A.,Simpson, J. M.,Xu, H.,Hayes, A. J.,Hardy, L. L.,Williams, M.,Rissel, C. Sustainability of Effects of an Early Childhood Obesity Prevention Trial Over Time: A Further 3-Year Follow-up of the Healthy Beginnings Trial. JAMA Pediatr.2015;169:543-51. | IV
611 | West, C. E.,Hernell, O.,Andersson, Y.,Sjostedt, M.,Hammarstrom, M. L. Probiotic effects on T-cell maturation in infants during weaning. Clin Exp Allergy.2012;42:540-9. | IV, DV
612 | Westphal, R.,Phillips, G.,Irwig, L. M. Infant care and feeding in an urban black population. S Afr Med J.1981;60:778-81. | DV, Date
613 | Weyermann, M.,Rothenbacher, D.,Brenner, H. Duration of breastfeeding and risk of overweight in childhood: a prospective birth cohort study from Germany. Int J Obes (Lond).2006;30:1281-7. | IV
614 | Wharf,S. G.,Fox,T. E.,Fairweather-Tait,S. J.,Cook,J. D. Factors affecting iron stores in infants 4-18 months of age. Eur J Clin Nutr.1997;51:504-9. | Design
615 | Whitehead, R. G.,Paul, A. A.,Ahmed, E. A. Weaning practices in the United Kingdom and variations in anthropometric development. Acta Paediatr Scand Suppl.1986;323:14-23. | Design, IV
616 | Whitehead, R. G.,Paul, A. A. Infant growth and human milk requirements. A fresh approach. Lancet.1981;2:161-3. | IV
617 | Whitten, C. F.,Stewart, R. A. The effect of dietary sodium in infancy on blood pressure and related factors. Studies of infants fed salted and unsalted diets for five months at eight months and eight years of age. Acta Paediatr Scand Suppl.1980;279:1-17. | IV
618 | Wiberger, M.,Eiben, G.,Lissner, L.,Mehlig, K.,Papoutsou, S.,Hunsberger, M. Children consuming milk cereal drink are at increased risk for overweight: The IDEFICS Sweden study, on behalf of the IDEFICS Consortium. Scand J Public Health.2014;42:518-24. | Design
619 | Wigg, N. R.,Tong, S.,McMichael, A. J.,Baghurst, P. A.,Vimpani, G.,Roberts, R. Does breastfeeding at six months predict cognitive development?. Aust N Z J Public Health.1998;22:232-6. | IV
620 | Wijga,A.,Vyas,U.,Vyas,A.,Sharma,V.,Pandya,N.,Nabarro,D. Feeding, illness and nutritional status of young children in rural Gujarat. Hum Nutr Clin Nutr.1983;37:255-69. | Design, IV
621 | Williams, D. M.,Martin, R. M.,Davey Smith, G.,Alberti, K. G.,Ben-Shlomo, Y.,McCarthy, A. Associations of infant nutrition with insulin resistance measures in early adulthood: evidence from the Barry-Caerphilly Growth (BCG) study. PLoS One.2012;7:e34161. | IV, DV
622 | Williams, J.,Wolff, A.,Daly, A.,MacDonald, A.,Aukett, A.,Booth, I. W. Iron supplemented formula milk related to reduction in psychomotor decline in infants from inner city areas: randomised study. Bmj.1999;318:693-7. | IV
623 | Winick, M. The role of early nutrition in subsequent development and optimal future health. Bull N Y Acad Med.1989;65:1020-5. | Design
624 | Winkelstein,M. L. Overfeeding in infancy: the early introduction of solid foods. Pediatr Nurs.1984;10:205-8, 236. | Design
625 | Wölfle, J. Growth and puberty in German children: is there still a positive secular trend? In reply..Consumption of milk as a vital factor in growth development. Melnik B, Dtsch Arzetebl 2009, volume 206. Deutsches Aerzteblatt International.2009;106:656-656. | Design
626 | Wright, C. M.,Parkinson, K. N.,Drewett, R. F. Why are babies weaned early? Data from a prospective population based cohort study. Arch Dis Child.2004;89:813-6. | DV
627 | Wright, C. M.,Parkinson, K.,Scott, J. Breast-feeding in a UK urban context: who breast-feeds, for how long and does it matter?. Public Health Nutr.2006;9:686-91. | IV
628 | Wright, M. J.,Bentley, M. E.,Mendez, M. A.,Adair, L. S. The interactive association of dietary diversity scores and breast-feeding status with weight and length in Filipino infants aged 6-24 months. Public Health Nutr.2015;18:1762-73. | Country
629 | Yew, K. S.,Webber, B.,Hodges, J.,Carter, N. J. Clinical inquiries: are there any known health risks to early introduction of solids to an infant’s diet?. J Fam Pract.2009;58:219-20. | Design
630 | Young RJ,Antonson DL,Ferguson PW,Murray ND,Merkel K,Moore TE. Neonatal and infant feeding: effect on bone density at 4 years. J Pediatr Gastroenterol Nutr.2005;41:88-93. | Design
631 | Yousafzai, A. K.,Rasheed, M. A.,Rizvi, A.,Armstrong, R.,Bhutta, Z. A. Effect of integrated responsive stimulation and nutrition interventions in the Lady Health Worker programme in Pakistan on child development, growth, and health outcomes: a cluster-randomised factorial effectiveness trial. Lancet.2014;384:1282-93. | Country
632 | Ystrom, E. Breastfeeding cessation and symptoms of anxiety and depression: a longitudinal cohort study. BMC Pregnancy Childbirth.2012;12:36. | IV, DV
633 | Zadik Z,Borondukov E,Zung A,Reifen R. Adult height and weight of breast-fed and bottle-fed Israeli infants. J Pediatr Gastroenterol Nutr.2003;37:462-7. | IV
634 | Zaman, S.,Jalil, F.,Saleemi, M. A.,Mellander, L.,Ashraf, R. N.,Hanson, L. A. Changes in feeding patterns affect growth in children 0-24 months of age living in socioeconomically different areas of Lahore, Pakistan. Adv Exp Med Biol.2002;503:49-56. | Country
635 | Zaman,S.,Ashraf,R. N.,Martines,J. Training in complementary feeding counselling of healthcare workers and its influence on maternal behaviours and child growth: a cluster-randomized controlled trial in Lahore, Pakistan. J Health Popul Nutr.2008;26:210-22. | IV, Country
636 | Zavaleta,N.,Kvistgaard,A. S.,Graverholt,G.,Respicio,G.,Guija,H.,Valencia,N.,Lonnerdal,B. Efficacy of an MFGM-enriched complementary food in diarrhea, anemia, and micronutrient status in infants. J Pediatr Gastroenterol Nutr.2011;53:561-8. | DV
637 | Zhang,J.,Shi,L.,Chen,D. F.,Wang,J.,Wang,Y. Effectiveness of an educational intervention to improve child feeding practices and growth in rural China: updated results at 18 months of age. Matern Child Nutr.2013;9:118-29. | IV
638 | Zhu, B.,Zhang, J.,Qiu, L.,Binns, C.,Shao, J.,Zhao, Y.,Zhao, Z. Breastfeeding Rates and Growth Charts--the Zhejiang Infant Feeding Trial. Int J Environ Res Public Health.2015;12:7337-47. | IV, DV
639 | Ziegler, E. E.,Fields, D. A.,Chernausek, S. D.,Steenhout, P.,Grathwohl, D.,Jeter, J. M.,Nelson, S. E.,Haschke, F. Adequacy of Infant Formula With Protein Content of 1.6 g/100 kcal for Infants Between 3 and 12 Months. J Pediatr Gastroenterol Nutr.2015;61:596-603. | IV
640 | Ziegler,E. E.,Fomon,S. J.,Nelson,S. E.,Rebouche,C. J.,Edwards,B. B.,Rogers,R. R.,Lehman,L. J. Cow milk feeding in infancy: further observations on blood loss from the gastrointestinal tract. J Pediatr.1990;116:11-8. | IV, DV
641 | Zive, M. M.,McKay, H.,Frank-Spohrer, G. C.,Broyles, S. L.,Nelson, J. A.,Nader, P. R. Infant-feeding practices and adiposity in 4-y-old Anglo- and Mexican-Americans. Am J Clin Nutr.1992;55:1104-8. | Design
642 | Zutavern, A.,Brockow, I.,Schaaf, B.,von Berg, A.,Diez, U.,Borte, M.,Kraemer, U.,Herbarth, O.,Behrendt, H.,Wichmann, H. E.,Heinrich, J. Timing of solid food introduction in relation to eczema, asthma, allergic rhinitis, and food and inhalant sensitization at the age of 6 years: results from the prospective birth cohort study LISA. Pediatrics.2008;121:e44-52. | DV