# List of abbreviations

Abbreviation: Full name
BF: Breastfed or breastfeeding
CFB: Complementary foods and beverages
FEP: Free erythrocyte protoporphyrin
FEG: Federal Expert Group
FF: Formula fed or formula feeding
Hb: Hemoglobin
Hct: Hematocrit
HHS: Department of Health and Human Services
ID: Iron deficiency
IDA: Iron deficiency anemia
MCV: Iron deficiency
NEL: Nutrition Evidence Library
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
P/B-24: Pregnancy and Birth to 24 Months Project
RCT: Randomized controlled trial
RDW: Red cell distribution width
SF: Serum ferritin
TEC: Technical Expert Collaborative
Tf: Transferrin
TfR: Transferrin receptor
TIBC: Total iron binding capacity
UK: United Kingdom
US: United States
USDA: United States Department of Agriculture
ZPP: Zinc-protoporphyrin