# WHAT IS THE RELATIONSHIP BETWEEN TYPES AND AMOUNTS OF COMPLEMENTARY FOODS/BEVERAGES AND MICRONUTRIENT STATUS?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between types and amounts of complementary foods and beverages and micronutrient status?

### What is the answer to the question?

- Strong evidence suggests that consuming complementary foods and beverages that contain substantial amounts of iron, such as meats or iron-fortified cereal, helps maintain adequate iron status or prevent iron deficiency during the first year of life among infants with insufficient iron stores or breastfed infants who are not receiving adequate iron from another source. However, the benefit of these types of complementary foods and beverages for infants with sufficient iron stores, such as those consuming iron-fortified infant formula, is less evident.
- There is not enough evidence to determine the relationship between other types/amounts of complementary foods and beverages containing lesser amounts of iron, such as fruits and vegetables, and iron status.
- Limited evidence suggests that consuming complementary foods and beverages that contain substantial amounts of zinc, such as meats or cereals fortified with zinc, supports zinc status during the first year of life, particularly among breastfed infants who are not receiving adequate zinc from another source. However, the benefit of these types of complementary foods for infants consuming fortified infant formula is less evident.
- Moderate evidence suggests that consuming complementary foods and beverages with differing fatty acid profiles, particularly long-chain polyunsaturated fatty acids, can influence fatty acid status.
- During the second year of life, good sources of micronutrients are still needed, but there is limited evidence to indicate which types and amounts of complementary foods and beverages are associated with adequate micronutrient status.
- There is not enough evidence to determine the relationship between types and amounts of complementary foods and beverages and vitamin B12, vitamin D, or folate status.

### Why was this question asked?

- This important public health question was identified and prioritized as part of the U.S. Department of Agriculture and Department of Health and Human Services Pregnancy and Birth to 24 Months Project.

### How was this question answered?

- A team of Nutrition Evidence Systematic Review staff conducted a systematic review in collaboration with a group of experts called a Technical Expert Collaborative

### What is the population of interest?

- Generally healthy infants and toddlers who were fed complementary foods and beverages from ages 0-24 months and had micronutrient status examined through 24 months of age

### What evidence was found?

- This review includes 31 studies.
- These studies compared different types or amounts of complementary foods and beverages and micronutrient status.
- Complementary foods and beverages are foods and beverages other than human milk or infant formula provided to an infant or young child.
- Studies need to consider other factors that could impact this relationship.

### How up-to-date is this review?

- This review includes literature from 1/1980 to 7/2016.

## FULL REVIEW

### Systematic review question

What is the relationship between types and amounts of complementary foods and beverages and micronutrient status?

### Conclusion statement

Strong evidence suggests that consuming complementary foods and beverages that contain substantial amounts of iron, such as meats or iron-fortified cereal, helps maintain adequate iron status or prevent iron deficiency during the first year of life among infants with insufficient iron stores or breastfed infants who are not receiving adequate iron from another source. However, the benefit of these types of complementary foods and beverages for infants with sufficient iron stores, such as those consuming iron-fortified infant formula, is less evident.

There is not enough evidence to determine the relationship between other types/amounts of complementary foods and beverages containing lesser amounts of iron, such as fruits and vegetables, and iron status.

Limited evidence suggests that consuming complementary foods and beverages that contain substantial amounts of zinc, such as meats or cereals fortified with zinc, supports zinc status during the first year of life, particularly among breastfed infants who are not receiving adequate zinc from another source. However, the benefit of these types of complementary foods for infants consuming fortified infant formula is less evident.

Moderate evidence suggests that consuming complementary foods and beverages with differing fatty acid profiles, particularly long-chain polyunsaturated fatty acids, can influence fatty acid status.

During the second year of life, good sources of micronutrients are still needed, but there is limited evidence to indicate which types and amounts of complementary foods and beverages are associated with adequate micronutrient status.

There is not enough evidence to determine the relationship between types and amounts of complementary foods and beverages and vitamin B12, vitamin D, or folate status.

### Grade

Strong – Iron status; Moderate – Fatty Acid status; Limited – Zinc status; Grade Not Assignable – Vitamin B12 status, Vitamin D status, Folate status

### Summary

- Complementary foods and beverages (CFB) were defined as foods and/or beverages (liquids, semisolids, and solids) other than human milk or infant formula provided to an infant or young child to provide nutrients and energy. This systematic review includes studies that compared different types or different amounts of CFB.
- Micronutrient status outcomes included iron, zinc, vitamin D, vitamin B12, folate, and/or fatty acid status from birth to 24 months of age.
- Thirty-one studies published between 01/1980 and 07/2016 met the inclusion criteria for this systematic review.
  ○ Most studies examined the relationship between types and/or amounts of CFB and iron status, and the CFB examined were largely limited to Fe-fortified cereals and meats.
  ○ Several studies examined zinc and fatty acid status and few studies examined vitamin D, vitamin B12, and folate.
- One randomized controlled trial, conducted in both breastfed (BF) and formula fed (FF) infants, showed that consuming meats or Fe- and/or Zn-fortified cereals as CFB generally protected against Fe deficiency anemia and supported Zn status in the first year of life, though evidence is more limited in the second year of life.
  ○ Among BF infants, meat and Fe- and Zn-fortified cereals supported iron and zinc status in later infancy. Meat provided a valuable source of trace minerals for BF infants who may not have been fed Fe- and Zn-fortified products; in fact, the frequency of meat consumption was associated with iron status in the first and second years of life.
  ○ In infants/toddlers whose diets already contained other bioavailable Fe and Zn sources (i.e. infant formulas and cereal fortified with iron and/or zinc), meat offered little additional benefit for Fe or Zn status, though it is an important source of bioavailable Fe and Zn.
- Dietary sources of fatty acids, particularly LC-PUFA, in CFB (i.e., oils, fish, meats, and eggs) influenced the plasma fatty acid profile of infants and toddlers.
- A limitation of some of the studies included in this systematic review was lack of accounting for whether infants were fed breast milk and/or infant formula, and other aspects of the overall diet, including consumption of fortified products and bioavailability of nutrients consumed. Another limitation is a lack of studies that examined vitamin D, vitamin B12, and folate.

### Description of the evidence

The systematic review that examined the relationship between the consumption of different types and amounts of CFB and micronutrient status from birth to 24mo of age includes 31 articles.

In general, the studies enrolled both girls and boys who were full term (>37wk) with a normal birthweight (≥2500g), and who were generally healthy, with many specifically excluding subjects with illnesses or conditions that could impact complementary feeding or nutritional status. In addition, most of the studies included subjects who were iron replete at baseline, though a few did include subject populations with relatively high prevalence of ID [1, 2]. Per the inclusion criteria, the studies were conducted in countries that were ranked as very high or high on the Human Development Index [3]. Most studies did not describe or confirm the racial/ethnic background of subjects, but they included subjects who were representative of the general population of the countries in which they were conducted. Several studies specified that the sample was majority white [4–10], 1 study included a sample that was 71% Jewish and 29% Bedouin [2], and 1 was conducted in Hispanic subjects [11].

The types of CFB introduced in these studies included meats, fortified and unfortified cereals, and a variety of other foods, for example, eggs, fruits and vegetables, and foods that varied in fatty acid content. Results for studies examining each of these types of food are discussed below.

#### Meat

Fifteen studies examined the relationship between consuming meat as a CFB and micronutrient status, including 8 RCTs reported in 9 publications [7, 12–18] and 7 prospective cohort studies [1, 2, 5, 6, 8, 19, 20] (Table 1).

Five studies examined the impact of consuming different amounts of meat on micronutrient status (iron and/or zinc status) and found few differences in iron or zinc status (Table 1). Two were RCTs [12, 13] and 3 were prospective cohort studies [1, 8, 19]. The studies compared different quantities of meat intake. Dube et al. [12] randomized BF and FF infants to either a low meat or high meat group for 6mo, and found no significant differences in any of the iron status measures assessed at ~10mo of age. Engelmann et al. [13] randomly assigned infants (partially BF) to low-meat and high-meat groups for 2mo (8 to 10mo of age), and reported that both groups experienced a significant decrease in Hb from 8 to 10mo of age, but that Hb decreased significantly more in the low meat compared to the high meat group. However, there were no significant differences between groups in SF, TfR, or serum zinc levels. Infants in this study also consumed iron from other less-bioavailable sources (formula, iron-fortified gruel and other CFB) but total iron intake did not differ between groups. Taylor et al. [8] found that consuming meat compared to not was associated with lower prevalence of low serum iron (iron <9umol/L) at 12mo of age, but found no significant associations with Hb<110g/L, SF <10ug/L, MCV, mean corpuscular hemoglobin concentration (MCHC), RDW, ZPP, or serum zinc. In this study, iron intake was similar between meat eaters and non-meat eaters at 4, 8, and 12mo, but was higher in non-meat eaters than meat eaters at 16, 20, and 24mo, and noted that a small percentage (2%) of dietary iron was from meat, with the vast majority coming from fortified infant formulas and foods. Michaelsen et al. [19] and Thorsdottir et al. [1] both found no significant associations between the amounts of meat consumed and iron status.

Several studies examined the duration or frequency of meat intake. Null findings were reported in 1 study looking at duration of meat intake and iron status, though it was noted that consumption of infant formula and iron-fortified cereal was common [5]. Three studies looked at whether the frequency of meat intake was related to micronutrient status, with all specifically interested in iron status [2, 6, 20]. Male et al. [6] reported no significant association between frequency of meat intake and iron status in subjects who were mostly FF. Urkin et al. [2] found that consuming meat less frequently (0-3 times/wk) compared to more frequently (4+ times/wk) was associated with significantly higher odds of ID or anemia in the second year of life in a population of toddlers, the majority of whom had been BF. Olaya et al. [20] examined frequency of red meat (>3 vs. <3 times/wk) intake in a group of infants during different time periods during the first year of life (6 to 8mo and 10 to 12mo). Results showed that higher frequency of red meat consumption from 6 to 8mo was also significantly associated with increased Hb between 6 and 12mo, and consuming red meat more frequently from 10 to 12mo was significantly associated with higher Hb, Hct, and MCV at 12mo, and a greater increase in Hb and MCV from 6 to 12mo. Infants in this study were exclusively BF through 4mo of age, and most continued BF throughout the study, though some were also given infant formula or cow’s milk.

Four studies also examined the effects of meat as a CFB compared to other types of foods on micronutrient status (Table 1). Three of these studies utilized fortified infant cereal [14–16] and 1 study used cow’s milk [7], both unfortified powdered whole cow’s milk and an iron-fortified powdered cow’s milk drink. Krebs et al. [15] compared meat to iron-fortified cereal consumed from 5-7mo of age in a US-based population of BF infants, and found no differences in Hb, SF, Hct, or plasma zinc at 9mo of age. In a different US-based trial, Krebs et al., [14, 16] compared meat to both iron-fortified cereal or iron- and zinc -fortified cereal consumed from 5-9mo of age, and found no significant differences in Hb, SF, TfR, prevalence of anemia, or in plasma zinc or exchangeable zinc pool size at 9mo of age. However, Krebs et al. [16] reported that total daily absorbed zinc was significantly higher among infants fed meat compared to those fed iron-fortified cereal without zinc fortification. In addition, Krebs et al. [14] also reported that significantly more infants in the meat group had elevated TfR levels (>1.8ug/dL) compared to the cereal groups, which may be indicative of increased risk of ID. Szymlek-Gay et al. [7] reported no significant differences in Hb, TfR, or measures of suboptimal iron status in BF and/or FF infants (12-20 mo of age) after 20wk of consuming meat, fortified cow’s milk, or non-fortified cow’s milk. The authors did find that SF was significantly higher among those who consumed meat or iron fortified milk, and body iron was higher among those who consumed fortified milk, compared to those who consumed non-fortified milk. However, infants in the meat group complied poorly with study protocol, consuming only 0.7 out of 2 recommended portions/day (d), such that the difference in meat intake between groups was minimal.

Two studies compared iron status among infants who were fed a combination of meat and cereal compared to those who received no intervention [17, 18]. Makrides et al. [17] reported no significant differences in iron status (Hb, SF, iron, Tf, Tf saturation) between exclusively BF infants who were fed a high-iron weaning diet (meat and iron-fortified cereal) or a standard weaning diet (recommendations to consume iron-fortified cereal) from 6 to 12mo of age. However, the intervention and control groups ended up consuming similar complementary feeding diets that contained comparable amounts of iron. Yeung et al. [18] reported no significant differences in incidence of iron depletion or early anemia among infants who received a combination of pureed meat and iron-fortified cereal compared to those who received no specific CFB intervention from 6 to 12mo of age. However, all subjects consumed cow’s milk, and the control group received iron supplements (~25%) and were fed diets similar to those of the intervention group (including meat and cereals), so there was ultimately little difference in CFB intake between the intervention and control groups.

#### Cereal

Thirteen studies examined the relationship between consuming different types of cereals (fortified and unfortified) (Table 2) as a CFB and micronutrient status, including 10 RCTs [10, 11, 14–18, 21–23] and 3 prospective cohort studies [1, 6, 19].

Several of these studies examined the impact of consuming different types and/or amounts of cereal on micronutrient status (Table 2). Three RCTs compared the effects on micronutrient status of consuming different types of cereals. Davidsson et al. [21] found no significant differences in iron status (Hb, SF, Hct) between exclusively formula fed infants who consumed 2 different types of unfortified cereal (wheat/soy or wheat/milk) at 2 levels of fiber content (low: 1.8%, 2%; high: 5.3%, 8%), each for 4wk. Infants enrolled in this study consumed each cereal without a washout period for a total of 16wk and were allowed to consume additional CFB upon request. Lind et al. [22] compared the effects of consuming iron fortified high-phytate cereal, reduced-phytate cereal, or infant formula and porridge from 6 to 12mo, and found that Hb at 12mo was significantly higher in the reduced phytate group compared to the infant formula porridge group. However, there were no significant differences between the groups in SF, MCV, or prevalence of low SF or anemia at 12mo. Infants enrolled in this study were mostly BF (75% at 6mo), and were all iron replete at baseline. Walter et al. [23] found that infants (up to age 15mo), both BF and FF, fed iron-fortified rice cereals compared to those fed non-fortified cereals had higher Hb and were significantly less likely to have Hb<105g/L and IDA. Walter et al. [23] also reported that infants fed iron-fortified formula with non-iron fortified cereal had significantly higher MCV and Tf saturation and significantly lower erythrocyte protoporphyrin compared to infants fed fortified cereal and non-fortified formula.

A number of studies, the design and results of which are described in the previous section, examined the effects of consuming cereal compared to meat as CFB [15–18] (Table 1, 2). In general, the studies found no significant differences in iron and zinc status outcomes between infants fed meat or fortified cereal, with the exception of one study [14, 16] reporting significantly higher zinc absorption among infants fed meat (vs. cereal fortified with iron, but not zinc) and significantly higher TfR levels in those fed cereal (vs. meat).

Two studies compared iron status among infants who were fed cereal compared to those who received no intervention [10, 11]. Hertrampf et al. [11] examined the effects on iron status among exclusively BF infants consuming iron-fortified cereal from 4 to 6mo of age compared to exclusively BF infants who received standard CFB recommendations (3mo: fruit, cereal, juice; 4mo: add vegetables and meat; 6mo: add legumes and eggs). At 9mo, the cereal vs. control group had significantly higher serum iron/TIBC, lower free erythrocyte protoporphyrin (FEP), and higher SF; but no significant differences in Hb and MCV. At 12mo, the cereal vs. control group had significantly higher Hb, MCV, serum iron/TIBC, and SF; but no significant differences in FEP. There were also no significant differences between groups in serum zinc or prevalence of low serum zinc (<10.7mol/L). Ziegler et al. [10] found that predominantly BF infants (4-24 mo of age) who received iron-fortified cereal had significantly higher SF and lower TfR/SF levels at 5.5, 7.5, 9, 12, and 15mo compared to those in a control group who received no dietary intervention (many of whom consumed commercially available infant cereals that were fortified with the less bioavailable electrolytic form of iron). However, the groups did not differ significantly on these measures at 18, 21, or 24mo, nor did they differ in Hb, TfR, RDW, or MCV at any time point. In this study, more than a third of the control group was receiving iron fortified infant formula from ~5 to 9mo, and formula intake in the cereal group, while lower at 5.5mo, was comparable to the control by 7.5mo and older.

Three prospective cohort studies reported mainly null results for the relationship between the amount or frequency of cereal consumption and iron status. Male et al. [6] examined frequency of cereal consumption from 9 to 12mo of age and found no significant associations with any measure of iron status assessed in infants who were mostly FF, and Michaelsen et al. [19] found no significant associations between the amounts of commercial and homemade porridge consumed and SF from 6 to 9mo of age in infants who were also mostly FF. However, while Thorsdottir et al. [1] did not find any significant associations between porridge or fortified breakfast cereal intake from 9 to 12mo of age and TfR, MCV, or TFR:log SF at 12mo of age among infants who were mostly BF, increased porridge intake and increased iron-fortified breakfast cereal intake were positively associated with Hb and SF at 12mo, respectively.

#### Other CFB

Ten additional studies looked at various different foods and beverages (Table 3) consumed as CFB and their relationship with micronutrient status, including five RCTs [7, 9, 24–26] and five prospective cohort studies [1, 4, 6, 19, 27].

##### Fruits and Vegetables

Three prospective cohort studies examined the association between consumption of fruits and vegetables as CFB and iron status. However, none of these studies described the specific vegetables or fruits included in analyses, nor did they describe which vegetables or fruits were most commonly consumed by subjects, making it difficult to determine the amount of iron this category of CFB contributed to iron intake. Male et al. [6] found no significant associations between frequency of fruit and vegetable intake from 9 to 12mo and iron status in a group of infants who were mostly FF (Hb, MCV, SF, Tf saturation, TfR, anemia, ID, or IDA). Michaelsen et al. [19] and Thorsdottir et al. [1] examined the amount of fruits and vegetables consumed from 6 to 9mo and 9 to12mo, respectively, and found no significant associations with iron status (change in SF, or log SF, MCV, Hb, TfR, Tfr:log SF) in infants who were either mostly FF or mostly BF.

##### Cow’s Milk

Two RCTs examined the effects of consuming different types of cow’s milk during the second year of life on micronutrient status [7, 9]. Szymlek-Gay et al. [7] reported no significant differences in Hb, TfR, or measures of suboptimal iron status in BF and/or FF infants (12-20 mo of age) after 20wk of consuming meat, fortified cow’s milk, or non-fortified cow’s milk. Virtanen et al. [9] randomly assigned FF toddlers (11-18mo of age) for 7mo to consume either low-fat cow’s milk, standard-fat cow’s milk, iron-fortified cow’s milk with 50% vegetable fat and vitamin C, or iron-fortified cow’s milk with 100% vegetable fat and vitamin C, and found no significant differences in any measure of iron status (Hb, MCV, SF, or TfR).

A third RCT [26] compared iron, zinc, and folate status in infants who were randomized to receive CFB (cornstarch and milk) from 6 to 12mo of age that was enriched with either milkfat globule membrane (MFGM) protein or skim milk proteins. While Hb at 12mo was significantly higher in the skim milk protein group compared to the MFGM group, there were no significant differences between groups in any of the following outcomes: SF, anemia (Hb<11g/dL), IDA (SF<10ug/L), serum zinc, zinc deficiency (<10.7umol/L), serum folate, or folate deficiency (<6.8mg/nL).

##### Fish

Two prospective cohort studies examined the association between the amount of fish consumed (grams/day) as CFB and micronutrient status; none of the studies examined types of fish. Michaelsen et al. [19] examined the amount of fish consumed from 6 to 9mo, and found no significant associations with iron status (change in SF). Thorsdottir et al. [1] examined the amount of fish consumed from 9 to 12mo, and found a positive association with SF, but no significant associations with any other measure of iron status (MCV, Hb, TfR, or Tfr:log SF).

##### Bread and Biscuits

Two prospective cohort studies examined the association between the amount of bread consumed (grams/day) as CFB and micronutrient status. Michaelsen et al. [19] found a negative association between bread consumption from 6 and 9mo and change in SF. Thorsdottir et al. [1] found no significant associations between bread intake from 9 to 12mo and any measure of iron status examined (SF, MCV, Hb, TfR, or Tfr:log SF).

An RCT [24] compared iron status in partially BF infants and toddlers (ages 6-13mo) who received a fortified (iron, zinc, vitamin A, calcium, folic acid) or non-fortified biscuit daily for 3mo. Results showed that while Hb did not change in the fortified biscuit group, but decreased in the unfortified biscuit group and this change was significantly different between groups. However, there were no significant differences between groups in SF, FEP, or ratio of FEP:Hb.

##### Other

Thorsdottir et al. [1] examined the relationship between several other foods/food groups consumed from 9 to 12mo and subsequent iron status, and reported that butter and cheese intake was negatively associated with SF, MCV, and Hb; but not with TfR or TfR:log SF. However, consumption of other CFB, including other dairy products (not including fluid cow’s milk, butter, or cheese), biscuits and crackers, cakes, and juices was not significantly associated with SF, CV, Hb, TfR, or TfR:log SF.

Makrides et al. [25] randomly assigned infants (BF and/or FF) to consume eggs (~ 4/wk, regular or omega-3 enriched) or receive no dietary intervention for 6mo, and reported no significant differences in Hb, SF, Tf, or prevalence of anemia. However, infants who received eggs had significantly higher plasma iron and Tf saturation compared to those in the control group who consumed a standard weaning diet of the parents’ choice (~2 eggs/wk).

Dagnelie et al. [4] prospectively examined infants (4 to 18 mo of age) fed a macrobiotic diet and compared them to those fed an omnivorous diet, and found the following differences in macrobiotic compared to omnivorous infants: MCHC, serum folate, and prevalence of subclinical and clinical/major rickets were higher; Hct, RBC, MCV, MCH, and plasma vitamin B12 and vitamin D were lower; and Hb, FEP, and SF did not differ.

Tantrecheewathorn et al. [27] examined whether consuming “adequate” complementary food was associated with risk of IDA. Adequacy was defined as a variety of food from various food groups (rice and grains, fruits, vegetables, milk, meat, eggs, fat), and adequate amounts of nutrients and energy compared with Thai Recommended Dietary Allowances. Results showed that risk of IDA (Hb<11g/dL, SF<12ng/ml) was significant increased among infants who consumed “inadequate complementary food” compared to those who consumed “adequate” complementary food.

#### CFB with Different Fatty Acid Profiles

Five studies, all of which were RCTs, examined the effects of consuming foods with varied fatty acid profiles on micronutrient and fatty acid (FA) status, focusing on long-chain polyunsaturated fatty acids (LC-PUFA) [25, 28–31] (Table 4).

In these studies, the types of foods tested and their fatty acid content varied, though they all focused on LC-PUFA, as did the results related to fatty acid status. Hoffman et al. [28] fed exclusively BF infants baby food with or without DHA from egg-yolk daily from 6 to 12mo of age, and measured iron status and fatty acid status. There were no significant differences between infants who received CFB with or without DHA in Hb, Hct, or MCV at 12mo. Infants fed DHA-enriched CFB had significantly higher levels of the following fatty acids at 12mo: DHA, DPA (n-6), DHA/DPA(n-6), and n-6/n-3 (all P<0.002); but there were no significant differences between groups in alpha-LNA, EPA, DPA (m-3), LA, 20:3, ARA, or 22:4.

Makrides et al. [25] fed infants regular eggs vs. eggs enriched with DHA, or assigned them to no dietary intervention (i.e., fed standard weaning diet of parents’ choice). Results showed that infants fed eggs enriched with DHA had significantly greater increases in DHA from 6 to 12mo and significantly higher mean DHA levels at 12mo compared to infants fed regular eggs or those in the control group. The authors also noted that overall, DHA levels were significantly higher in BF infants compared to FF infants, though FF infants fed n-3 eggs had DHA levels that were not significantly different from BF infants in the control group. In addition, there were no significant differences between any of the groups in AA at 12mo.

Libuda et al. [29] fed infants CFB with ALA-rich rapeseed oil, fish (salmon containing DHA), or CFB with linoleic acid (LA)-containing corn oil. The authors reported that infants fed CFB with rapeseed oil had significantly higher ALA and ALA:LA ratio compared to those fed CFB with corn oil, but there were no significant differences between groups in any other measure of fatty acid status (DHA, EPA, AA, LA, n3 LC PUFA, n3 PUDA, n3 LC-PUFA: n6 LC-PFA, n3 PUFA: n6 PUFA, EPA: AA). In addition, infants fed fish had significantly higher DHA, EPA, n3 LC-PUFA, n3 PUFA, n3 LC-PUFA: n6 LC-PUFA, PUFA: n6 PUFA, ALA:LA, and EPA:AA compared to the group fed CFB with corn oil, but LA, AA, and ALA did not differ significantly between groups.

Schwartz et al. [30] fed exclusively BF infants baby food (meat-based) with either rapeseed (canola) oil (LA 20%; ALA 9%; LA/ALA 2.2; LA/ALA ratio of 3.9) or corn oil (LA 55% of total fatty acid; ALA 1%; LA/ALA 55); LA/ALA ratio of 35.7) daily from 6 to 10mo of age. Infants fed CFB with rapeseed oil vs. corn oil had significantly higher levels of: n-3 fatty acids (P<0.001), EPA (P<0.001), and DHA at 10mo (P=0.0157). Infants fed CFB with corn oil vs. rapeseed oil had higher levels of: n-6 fatty acids (P=0.0012), LA (P=0.0002), n-6/n-3 (P<0.001), n-6/n-3 LCPUFA (P=0.0130), AA/EPA (P<0.001), and LA/ALA at 10mo (P=0.011). There were no significant differences between groups in GLA, ALA, or AA.

Svahn et al. [31] gave toddlers (12 to 15mo of age) cow’s milk that was either low-fat, standard fat, made with 50% vegetable fat from rapeseed oil (partial vegetable fat, PVF), or made with 100% vegetable fat from palm-, coconut- and soybean oil (full vegetable fat, FVF). Results showed that LA was significantly greater in the FVF group and ALA was greater in the PVF group compared to the low-fat and standard fat cow’s milk groups. In additional, total trans FA were lower in the PVF and FVF groups compared to the standard fat cow’s milk group. However, there were no differences between groups in AA or DHA levels.

### Evidence synthesis

A number of conclusions were drawn from the body of evidence examining the relationship between types and amounts of CFB and micronutrient status:

- Strong evidence suggests that consumption of CFB that contain substantial amounts of iron, such as meats or iron-fortified cereal, helps maintain adequate iron status or prevent iron deficiency during the first year of life among infants at risk for insufficient iron stores or low dietary intake (e.g. BF infants who are not receiving adequate iron from another source). However, the benefit of these types of CFB for infants with sufficient iron stores, such as those consuming iron-fortified infant formula, is less evident.
- Not enough evidence is available to determine the relationship between other types/amounts of CFB containing lesser amounts of iron, such as fruits and vegetables, and iron status.
- Limited evidence suggests that consuming CFB that contain substantial amounts of zinc, such as meats or cereals fortified with zinc, supports zinc status during the first year of life, particularly among BF infants who are not receiving adequate zinc from another source. However, the benefit of these types of CFB for infants consuming infant formula fortified with zinc is less evident.
- Moderate evidence suggests that consuming CFB with differing fatty acid profiles, particularly long-chain polyunsaturated fatty acids, can influence fatty acid status.
- During the second year of life, good sources of micronutrients are still needed, but there is limited evidence to indicate which types and amounts of CFB are associated with adequate micronutrient status.
- There is not enough evidence to determine the relationship between types and amounts of CFB and vitamin B12, vitamin D, or folate status.

The studies in this systematic review suggest that infants can accept and consume a wide range of different types of CFB. This was measured specifically by Krebs et al. [15], who found that acceptance of the study foods was similar between cereal and beef groups. Other studies demonstrated acceptability by good compliance with assigned diets or had free-living infants who were reported to consume a variety of foods as CFB. However, despite the substantial body of generalizable evidence available, including several RCTs designed to directly address this systematic review question, drawing conclusions is difficult due to inconsistency in study design and CFBs examined. The different types and/or amounts of CFB compared in this body of evidence, as well as the outcomes measured, varied widely from study to study. Studies differed in terms of the age at which CFB were introduced, timing of assessment of micronutrient status, duration of interventions, as well as the duration of monitoring of CFB intake and age of follow-up.

One particularly noteworthy limitation across many of the studies included in this systematic review was lack of comprehensive adjustment for feeding practices aside from complementary feeding, including whether infants were BF or consumed infant formula, particularly iron-fortified infant formula, were mixed fed (BF and FF), or were fed cow’s milk. In many cases, infants in the comparison groups consumed different types of foods but had diets with similar overall micronutrient composition, making null findings less meaningful. Most studies enrolled a generally healthy population of infants who were iron replete, or had “normal” baseline micronutrient levels. In general, risk of iron or zinc deficiency was low at the beginning of the complementary feeding period due to adequate stores of both iron and zinc at birth. Risk of iron and zinc deficiency typically increases in later infancy, particularly among BF infants who are not consuming fortified infant formula and/or obtaining adequate amounts of these specific nutrients in their CFB. In addition, as BF and FF infants transition from breast milk or infant formula to unfortified cow’s milk, typically after 12 months of age, changes in iron and/or zinc status can occur, making consumption of iron and zinc - containing CFB important for this age group as well.

A number of studies did avoid the confounding effects of infant formula by including infants who were exclusively BF prior to introduction of CFB, and who continued to receive human milk throughout the study (i.e., few infants were introduced to either fortified infant formula or cow’s milk) [1, 2, 14–17, 20, 23]. Many studies suggested that BF infants who consumed iron-containing CFB, whether meat or iron-fortified cereal, maintained adequate iron status through the end of the first year of life. And, further, BF infants who consumed CFB with iron and zinc, such as meat or cereal fortified with iron and zinc, maintained adequate zinc status as well. While some of the null associations with iron status reported in cohort studies [1, 6, 19] suggest that consumption of fruits and vegetables may not displace intake of iron-rich foods, this needs further exploration. In addition, more information is needed regarding the overall contribution of fruits and vegetables to iron intake and/or bioavailability, and whether those higher in iron are commonly consumed as CFB.

Furthermore, while most studies examined iron status as the primary outcome of interest, there was substantial variation in the biomarkers or combinations of biomarkers used to assess iron status. In addition, most studies examined micronutrient status outcomes during the first year of life, with only a few studies examining outcomes during the second year of life (14 to 24mo) [4, 5, 7, 8, 10, 23]. For example, both Hb and SF levels were included as biomarkers in most studies except 1 that measured only SF [19]. Many studies included at least a third indicator of iron status related to either red blood cell function (e.g., Hct, MCV, FEP, ZPP), iron homeostasis (e.g., TfR, Tf saturation, TIBC), and/or the presence of anemia or IDA based on various biomarker values. While SF levels strongly correlate with iron storage and Hb levels strongly correlate with ID, the majority of infants from all studies had sufficient SF and Hb levels upon enrollment (i.e., participants already had sufficient iron status). Therefore, it is likely that any good source of iron can maintain sufficient iron status if deficiency at baseline is absent. When examining zinc status as an outcome, all studies used venous or capillary blood samples to assess plasma or serum zinc. Plasma/serum zinc as a biomarker of zinc status has low sensitivity, is influenced by inflammatory status, and does not adequately reflect zinc homeostasis. Therefore, the results related to the effect of types of CFB on zinc status outcomes should be considered with caution. Only 1 study assessed zinc homeostasis [16] by measuring total absorbed zinc from CFB and the exchangeable zinc pool and demonstrated poorer zinc status in infants randomized to infant cereal not fortified with zinc.

While the majority of studies examined iron and/or zinc status as the primary outcomes of interest, there were several RCTs that compared the effects of consuming CFB with different fatty acid profiles on fatty acid status. There was variation across studies in the CFB tested and the outcomes considered, but there was consistency in the finding that fatty acid content of CFB had a significant impact on infants’ and toddlers’ fatty acid status.

The RCTs in this review had fewer concerns related to internal validity, were more likely to be the true effects of the types and amounts of CFB consumed and micronutrient status compared to the results from the prospective cohort studies. However, in many cases it was important to consider the nutrient content of the CF diet consumed by the control or comparison group when interpreting null findings, as several indicated that these diets were often similar in nutrient content to the experimental CF diet. Several of the cohort studies have major methodological limitations related to confounding bias from factors such as education, socioeconomic status, maternal age, race/ethnicity, child sex, birth size, and gestational age. Few of the cohort studies described baseline characteristics of subjects, making it impossible to determine whether the comparison groups differed on any of these confounders at baseline, and few adjusted for many of the key confounders listed above in outcome analyses. In addition, it is likely that several studies did not include sufficient sample size to adequately analyze results from certain sub-sets of study subjects.

### Research recommendations

In order to better assess the relationship between different types and/or amounts of CFB and micronutrient status, future research that addresses this topic should:

- Include both randomized controlled trials and prospective cohort studies with sufficient sample sizes, that clearly define types and amounts of CFB that are introduced and examine micronutrient status outcomes of public health concern, such as iron, zinc, vitamin D, vitamin B-12, folate, and/or fatty acid status
- Account for whether infants were fed breast milk and/or infant formula, and other aspects of the overall diet, including consumption of fortified products and bioavailability of nutrients consumed.
- Adjust for key confounding factors in observational studies, including: education, socioeconomic status, maternal age, race/ethnicity, child sex, birth size, gestational age, birth weight, post-natal growth, and iron stores at birth
- Include diverse populations with varying racial/ethnic and socioeconomic backgrounds, and with increased risk of poor nutritional status (including ID and IDA).
- Include sufficient duration of follow-up, through the second year of life and beyond, to assess the longer term effects (including functional outcomes) of complementary feeding.

Table 1 Description of studies examining the relationship between consuming meat as a complementary food and micronutrient status

Reference; n; country; milk feeding practices | Intervention or exposure | Results for iron status | Results for zinc status
Randomized Controlled Trials
Dube, 2010 [12]; 97; Germany; BF and/or FF | High Meat Group: Beef and poultry meals, 12% for 6mo (4 to 10mo) | Hb at 10mo: 12.0g/dL, 95% CI: 11.7, 12.3 vs. 11.7g/dL, 95% CI: 11.3, 12; P=0.0563
Dube, 2010 [12]; 97; Germany; BF and/or FF | Low Meat Group: Beef and poultry meals, 8% for 6mo (4 to 10mo) | Hct, MCV, MCHC, SF, TfR, ZPP, serum iron at 10mo: No significant group differences
Engelmann, 1998 [13]; N=41; Denmark; Partially BF | Low Meat Group: Beef, pork, lamb, turkey, or cod, 10g/d for 2mo (8 to 10mo) | Hb from 8 to 10mo: −0.49 g/dL, 95% CI: −1.29, 0.56 vs. −0.06 g/dL, 95% CI: −1.21, +0.73; P=0.0008 | Serum Zinc at 10mo or change from 8 to 10mo: No significant group differences
Engelmann, 1998 [13]; N=41; Denmark; Partially BF | High Meat Group: beef, pork, lamb, turkey, or cod, 27g/d for 2mo (8 to 10mo) | SF, SF<10μg/l, TfR at 10mo or change from 8 to 10mo: No significant group differences
Krebs, 2006 [15]; 72; US; Exclusively BF | Meat Group: Pureed beef ad libitum for 2mo (5 to 7mo) | Hb, SF, or Hct at 9mo: No significant group differences | Plasma Zinc at 9mo: No significant group differences
Krebs, 2006 [15]; 72; US; Exclusively BF | Cereal Group: Iron-fortified rice cereal ad libitum for 2mo (5 to 7mo)
Krebs, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22648720) [16]; 42; US; Exclusively BF | Meat Group: Pureed beef, 1-2 jar/d for 3-4mo (5 to 9-10mo) | | Fractional zinc absorption at 9-10mo: 0.22±0.01, 0.21±0.02 vs. 0.33±0.04, P=0.003
Krebs, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22648720) [16]; 42; US; Exclusively BF | Iron-Zinc Fortified Cereal Group: Iron + zinc fortified cereal, 1-2 serving/d for 3-4mo (5 to 9-10mo) | | Total absorbed zinc at 9-10mo: Higher in the meat, iron-zinc fortified cereal groups vs. iron-fortified cereal group; P<0.05
Krebs, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22648720) [16]; 42; US; Exclusively BF | Iron-Fortified Cereal Group: Iron-fortified cereal, 1-2 serving/d for 3-4mo (5 to 9-10mo) | | Exchangeable zinc pool at 9-10mo: No significant group differences
Krebs, 2013 [14]; 41; US; Exclusively BF | Meat Group: Pureed beef, 1-2 jar/d for 3-4mo (5 to 9-10mo) | TfR>1.8ug/dL at 9mo: 64% (meat) vs. 22% (cereal groups); P=0.03
Krebs, 2013 [14]; 41; US; Exclusively BF | Iron-Zinc Fortified Cereal Group: Iron + zinc fortified cereal, 1-2 serving/d for 3-4mo (5 to 9-10mo) | SF, Hb, low SF (<15ug/L), anemia (Hb<11.5g/dL), TfR at 9mo: No significant group differences
Krebs, 2013 [14]; 41; US; Exclusively BF | Iron-Fortified Cereal Group: Iron-fortified cereal, 1-2 serving/d for 3-4mo (5 to 9-10mo)
Makrides, 1998 [17]; 62; Australia; Exclusively BF | High-Iron Weaning Diet Group: Advice to offer red meat and iron-fortified cereal for 6mo (6 to 12mo) | Hb, SF, iron, Tf, Tf saturation at 12mo: No significant group differences
Makrides, 1998 [17]; 62; Australia; Exclusively BF | Control Weaning Diet Group: Standard nutritional advice (iron-fortified cereal from 4-6mo)
Szymlek-Gay, 2009 [7]; 205; New Zealand; BF or cow’s milk | Meat Group: Red meat, 2 portions/d for 20wk (baseline 12-20mo) | SF: Meat, fortified milk groups (29ug/L, 95% CI: 1.02, 1.63; P=0.033, 1.68ug/L, 95% CI: 1.27, 2.24; P<0.001) vs. non-fortified milk group
Szymlek-Gay, 2009 [7]; 205; New Zealand; BF or cow’s milk | Fortified Milk Group: Replaced cow’s milk with iron-fortified powdered cow’s milk | Body iron: Fortified milk group (1.9mg/kg, 95% CI: 0.8, 3.1; P<0.001) vs. non-fortified milk group
Szymlek-Gay, 2009 [7]; 205; New Zealand; BF or cow’s milk | Non-Fortified Milk Group: Replaced regular cow’s milk with non-fortified powdered cow milk, | Hb, TfR, depleted iron stores, iron-deficient erythropoiesis, IDA: No significant group differences
Yeung, 2000 [18]; 103; Canada; Cow’s milk fed | Treatment Group: Pureed meat, 1-2 jars/d, and iron -fortified infant cereals, 2/3 cup/d, for 6mo (6 to 12mo) | Iron depletion (SF<10 μg/L) or anemia (Hb<11.0g/dL): No significant group differences
Yeung, 2000 [18]; 103; Canada; Cow’s milk fed | Control Group: No intervention
Prospective Cohort Studies
Freeman, 1998 [5]; 76; Ireland | Age of meat introduction: Not defined | Hb, SF, or MCV at 12 or 24mo: No significant associations
Male, 2001 [6]; 488; Austria, Germany, Greece, Hungary, Ireland, Italy, Portugal, Spain, Sweden | Frequency of meat consumption: Never, 1–2 times/wk, weekly, almost daily from 9 to 12mo | Hb, MCV, SF, TSAT, TfR, anemia, ID, IDA at 12mo: No significant associations
Michaelsen, 1995 [19]; 84; Denmark | Amount of meat consumed: g/d | SF from 6-9mo: No significant associations
Olaya, 2013 [20]; 76; Colombia | Frequency of red meat consumption: Mean times/wk from 6 to 8mo | Hb from 6 to 12mo: Increased red meat frequency, r=0.24, P=0.05
Olaya, 2013 [20]; 76; Colombia | | Hct, MCV, SF: No significant associations
Olaya, 2013 [20]; 76; Colombia | Mean times/wk from 8 to 10mo | Hb from 6 to 12mo: r=0.32, P=0.006
Olaya, 2013 [20]; 76; Colombia | | Hct from 6 to 12mo: r=0.34, P=0.003
Olaya, 2013 [20]; 76; Colombia | | SF from 6 to 12mo: r=0.30, P=0.02
Olaya, 2013 [20]; 76; Colombia | | MCV: No significant associations
Olaya, 2013 [20]; 76; Colombia | Mean times/wk from 10 to 12mo | Hb, Hct, MCV, SF: No significant associations
Olaya, 2013 [20]; 76; Colombia | Mean times/wk from 6 to 12mo | Hb from 6 to 12mo: r=0.307, P=0.008
Olaya, 2013 [20]; 76; Colombia | | Hct from 6 to 12mo: r=0.27, P=0.02
Olaya, 2013 [20]; 76; Colombia | | MCV, SF: No significant associations
Olaya, 2013 [20]; 76; Colombia | >3 vs. <3 times/wk from 6 to 8mo | MCV at 12mo: 72.5±4.4fL vs. 69.6±3.7fL; P=0.02
Olaya, 2013 [20]; 76; Colombia | | Higher MCV from 6 to 12mo: P<0.05
Olaya, 2013 [20]; 76; Colombia | >3 vs. <3 times/wk from 10 to 12mo | Higher Hb at 12mo: P=0.016
Olaya, 2013 [20]; 76; Colombia | | Higher Hb from 6 to 12mo: P<0.01
Olaya, 2013 [20]; 76; Colombia | | Higher Hct at 12mo: P=0.03
Taylor, 2004 [8]; 149 at 4mo, 149 at 12mo, 130 at 24mo; UK | Amount of meat (beef, lamb, pork, game, poultry, fish) consumed: 13-767g, 768-1095g, 1096-3204g, nonmeat eaters from 4 to 24mo | Hb<110g/L, SF <10ug/L, MCV, MCHC, RDW, ZPP at 4, 12, or 24mo: No significant associations | Zinc at 4, 12, or 24mo: No significant associations
Taylor, 2004 [8]; 149 at 4mo, 149 at 12mo, 130 at 24mo; UK | | Low serum iron (<9.0umol/L) at 12mo: Inverse association, data not provided; P<0.023
Thorsdottir, 2003 [1]; 114; Iceland | Amount of meat consumed: g/d from 9 to 12mo | Hb, SF, TfR, MCV, Tfr:log SF at 12mo: No significant associations
Urkin, 2007 [2]; 142; Israel | Frequency of meat consumption: 0-3 vs. ≥4 times/wk at 17mo (12-24mo) | ID or anemia at 24mo: 2.32. 95% CI: 1.06, 5.07; P=0.034

Table 2 Description of studies examined the relationship between consuming cereal as a complementary food and micronutrient status

Reference; n; country; milk feeding practices | Intervention or exposure | Results for iron status | Results for zinc status
Randomized Controlled Trials
Davidsson, 1996 [21]; 57; Scotland; FF | Wheat/Soy, High Fiber: Wheat/soy cereal with 8% fiber, ad libitum for 4wk (crossover, no washout) | Hb, SF, or HCT after 16wk: No significant group differences
Davidsson, 1996 [21]; 57; Scotland; FF | Wheat/Soy, Low Fiber: Wheat/soy cereal with 1.8% fiber, ad libitum for 4wk
Davidsson, 1996 [21]; 57; Scotland; FF | Wheat/Milk, High Fiber: Wheat/milk cereal with 5.3% fiber, ad libitum for 4wk
Davidsson, 1996 [21]; 57; Scotland; FF | Wheat/Milk, Low Fiber: Wheat/milk cereal with 2% fiber, ad libitum for 4wk
Hertrampf, 1990 [11]; 188; Chile; Exclusively BF | Cereal group: Iron-fortified cereal, 20-40g/d from 4 to 6mo | SF at 9mo: 16 vs. 12ug/l; P<0.03
Hertrampf, 1990 [11]; 188; Chile; Exclusively BF | Control group: Standard complementary feeding recommendations | SF at 12mo: 14 vs. 11ug/l; P<0.03
Hertrampf, 1990 [11]; 188; Chile; Exclusively BF | | Serum iron/TIBC at 9mo: 15.1% vs. 12.6%; P<0.001
Hertrampf, 1990 [11]; 188; Chile; Exclusively BF | | Serum iron/TIBC at 12mo: 14.5% vs. 11.2%; P<0.002
Hertrampf, 1990 [11]; 188; Chile; Exclusively BF | | FEP at 9mo: 1.59 vs. 1.80umol/l, P<0.004
Hertrampf, 1990 [11]; 188; Chile; Exclusively BF | | Hb at 12mo: 122 vs. 117g/l; P<0.003
Hertrampf, 1990 [11]; 188; Chile; Exclusively BF | | MCV at 12mo: 69 vs. 71fl, P<0.03
Hertrampf, 1990 [11]; 188; Chile; Exclusively BF | | Hb, MCV at 9mo, FEP at 12mo: No significant group differences
Krebs, 2006 [15]; 72; US; Exclusively BF | Meat Group: Pureed beef ad libitum for 2mo (5 to 7mo) | Hb, SF, or Hct at 9mo: No significant group differences | Plasma Zinc at 9mo: No significant group differences
Krebs, 2006 [15]; 72; US; Exclusively BF | Cereal Group: Iron-fortified rice cereal ad libitum for 2mo (5 to 7mo)
Krebs, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22648720) [16]; 42; US; Exclusively BF | Meat Group: Pureed beef, 1-2 jar/d for 3-4mo (5 to 9-10mo) | | Fractional zinc absorption at 9-10mo: 0.22±0.01, 0.21±0.02 vs. 0.33±0.04, P=0.003
Krebs, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22648720) [16]; 42; US; Exclusively BF | Iron-Zinc Fortified Cereal Group: Iron + zinc fortified cereal, 1-2 serving/d for 3-4mo (5 to 9-10mo) | | Total absorbed zinc at 9-10mo: Higher in the meat, iron-zinc fortified cereal groups vs. iron-fortified cereal group; P<0.05
Krebs, 2012 (https://www.ncbi.nlm.nih.gov/pubmed/22648720) [16]; 42; US; Exclusively BF | Iron-Fortified Cereal Group: Iron-fortified cereal, 1-2 serving/d for 3-4mo (5 to 9-10mo) | | Exchangeable zinc pool at 9-10mo: No significant group differences
Krebs, 2013 [14]; 41; US; Exclusively BF | Meat Group: Pureed beef, 1-2 jar/d for 3-4mo (5 to 9-10mo) | TfR>1.8ug/dL at 9mo: 64% (meat) vs. 22% (cereal groups); P=0.03
Krebs, 2013 [14]; 41; US; Exclusively BF | Iron-Zinc Fortified Cereal Group: Iron + zinc fortified cereal, 1-2 serving/d for 3-4mo (5 to 9-10mo) | SF, Hb, low SF (<15ug/L), anemia (Hb<11.5g/dL), TfR at 9mo: No significant group differences
Krebs, 2013 [14]; 41; US; Exclusively BF | Iron-Fortified Cereal Group: Iron-fortified cereal, 1-2 serving/d for 3-4mo (5 to 9-10mo)
Lind, 2003 [22]; 267; Sweden; BF and/or FF | Commercial Phytate Group: Commercial milk-cereal (iron-fortified oat and wheat cereal drink/porridge) with regular phytate levels from 6 to 12mo | Hb at 12mo: Reduced phytate vs. infant formula group (120 vs. 117g/L); P=0.05 | Serum zinc, low serum zinc (<10.7mol/L) at 12mo: No significant group differences
Lind, 2003 [22]; 267; Sweden; BF and/or FF | Reduced Phytate Group: Phytate-reduced milk-cereal-drink/porridge from 6 to 12mo | MCV, SF, low SF (SF<12ug/l), anemia ((Hb<10.0g/dL) at 12mo: No significant group differences
Lind, 2003 [22]; 267; Sweden; BF and/or FF | Infant formula group: Infant formula and porridge from 6 to 12mo
Makrides, 1998 [17]; 62; Australia; Exclusively BF | High-Iron Weaning Diet Group: Advice to offer red meat and iron-fortified cereal for 6mo (6 to 12mo) | Hb, SF, iron, Tf, Tf saturation at 12mo: No significant group differences
Makrides, 1998 [17]; 62; Australia; Exclusively BF | Control Weaning Diet Group: Standard nutritional advice (iron-fortified cereal from 4-6mo)
Walter, 1993 [23]; 444 at 8mo; 370 at 12mo; 340 at 15mo; Chile; FF or BF | Group 1: Iron-fortified rice cereal and unfortified formula for 11mo (from 4 to 15mo) | Hb at 8, 12, and 15 mo: Group 1>2; P<001
Walter, 1993 [23]; 444 at 8mo; 370 at 12mo; 340 at 15mo; Chile; FF or BF | Group 2: Non-fortified rice cereal and unfortified formula for 11mo (from 4 to 15mo) | Hb at 8, 12, and 15mo: Group 1, 3, no significant differences
Walter, 1993 [23]; 444 at 8mo; 370 at 12mo; 340 at 15mo; Chile; FF or BF | Group 3: Non-fortified rice cereal and fortified formula for 11mo (from 4 to 15mo) | Hb at 12 and 15mo: Group 4>5; P<0.05
Walter, 1993 [23]; 444 at 8mo; 370 at 12mo; 340 at 15mo; Chile; FF or BF | Group 4: Iron -fortified rice cereal and breast milk for 11mo (from 4 to 15mo) | Hb<105 g/L: Group 1<2, P<0.05; Group 3 < 2, P<0.001; Group 4<5, P<0.025
Walter, 1993 [23]; 444 at 8mo; 370 at 12mo; 340 at 15mo; Chile; FF or BF | Group 5: Non-fortified rice cereal and breast milk for 11mo (from 4 to 15mo) | IDA (Hb<110g/L + MCV<70, SAT<10%, and/or SF<10 pg/L: Groups 1, 3<2 (8%, 4% vs. 24%), P<0.05; Group 4<5 (13% vs. 27%) P<0.01
Walter, 1993 [23]; 444 at 8mo; 370 at 12mo; 340 at 15mo; Chile; FF or BF | | MCV, Tf saturation: Group 3>1 (P=NR)
Walter, 1993 [23]; 444 at 8mo; 370 at 12mo; 340 at 15mo; Chile; FF or BF | | Erythrocyte protoporphyrin: Group 1>3 (P=NR)
Yeung, 2000 [18]; 103; Canada; Cow’s milk fed | Treatment Group: Pureed meat, 1-2 jars/d, and iron -fortified infant cereals, 2/3 cup/d, for 6mo (6 to 12mo) | Iron depletion (SF<10 μg/L) or anemia (Hb<11.0g/dL): No significant group differences
Yeung, 2000 [18]; 103; Canada; Cow’s milk fed | Control Group: No intervention
Ziegler, 2009 [10]; 93 US; Exclusively BF | Iron-fortified Cereal Group: Iron-fortified cereal) for 5mo (from 4 to 9mo) | SF at 5.5, 7.5, 9, 12, and 15mo: 82 vs. 42, 61 vs. 36, 48 vs. 28, 39 vs. 25, 28 vs. 28ug/L; P<0.05
Ziegler, 2009 [10]; 93 US; Exclusively BF | Control Group: No intervention | SF at 18, 21, and 24mo: No significant group differences
Ziegler, 2009 [10]; 93 US; Exclusively BF | | ln[TfR/SF] 5.5, 7.5, 9, 12, and 15mo: Cereal < control group; P<0.05
Ziegler, 2009 [10]; 93 US; Exclusively BF | | ln[TfR/SF] at 18, 21, or 24mo: No significant group differences
Ziegler, 2009 [10]; 93 US; Exclusively BF | | Hb, TfR, RDW, or MCV: No significant group differences
Prospective Cohort Studies
Male, 2001 [6]; 488; Austria, Germany, Greece, Hungary, Ireland, Italy, Portugal, Spain, Sweden | Frequency of cereal consumption: Never, 1–2 times/wk, weekly, almost daily from 9 to 12mo | MCV: β=0.13; P<0.01
Male, 2001 [6]; 488; Austria, Germany, Greece, Hungary, Ireland, Italy, Portugal, Spain, Sweden | | SF: β=0.23; P<0.001
Male, 2001 [6]; 488; Austria, Germany, Greece, Hungary, Ireland, Italy, Portugal, Spain, Sweden | | TfR: β=0.16; P<0.05
Male, 2001 [6]; 488; Austria, Germany, Greece, Hungary, Ireland, Italy, Portugal, Spain, Sweden | | Hb, Tf saturation, anemia, ID, IDA: No significant associations
Michaelsen, 1995 [19]; 84; Denmark | Amount of industrial and home-made porridge consumed: 100g/d | SF from 6 to 9mo: No significant associations
Thorsdottir, 2003 [1]; 114; Iceland | Amount of porridge consumed: g/d from 9-12mo | Hb at 12mo: 0.102 (SD=0.042), P=0.017
Thorsdottir, 2003 [1]; 114; Iceland | | No associations with SF, TfR, MCV, TfR:log SF at 12mo: No significant associations
Thorsdottir, 2003 [1]; 114; Iceland | Amount of fortified breakfast cereal consumed: g/d from 9-12mo | SF at 12mo: 0.010 (SD=0.004), P=0.009
Thorsdottir, 2003 [1]; 114; Iceland | | No associations with Hb, TfR, MCV, TfR:log SF at 12mo: No significant associations

Table 3 Description of studies examined the relationship between consuming complementary foods other than meat or cereal and micronutrient status

Reference; n; country; milk feeding practices | Intervention or exposure | Results for iron status | Results for zinc status | Results for vitamin B12 and folate status | Results for Vitamin D status
Randomized Controlled Trials
Liu, 1993 [24]; 164; China; Partially BF | Fortified Biscuit Group: Fortified (with iron, zinc, vitamin A, calcium, and folic acid) biscuits daily for 3mo (baseline 6-13mo) | Hb: −0.79g/L, P<0.01 in unfortified biscuit group
Liu, 1993 [24]; 164; China; Partially BF | Unfortified Biscuit Group: Unfortified biscuits daily for 3mo (baseline 6-13mo) | FEP, FEP:Hb, SF: No significant group differences
Makrides, 2002 [25]; 137; Australia; BF and FF | Egg Groups: Regular or DHA-enriched eggs, 4 yolks/wk for 6mo (6 to 12mo) | Plasma iron at 12mo in BF and FF infants: 10.5 vs. 8.3g/L, P<0.05
Makrides, 2002 [25]; 137; Australia; BF and FF | Control group: No intervention | Tf saturation at 12mo in BF infants: 14.3% vs. 10.8%, P<0.05
Makrides, 2002 [25]; 137; Australia; BF and FF | | Tf saturation at 12mo in FF infants: 14.6% vs. 11.6%, P<0.05
Makrides, 2002 [25]; 137; Australia; BF and FF | | Hb, SF, and Tf values, or anemia at 12mo: No significant group differences
Szymlek-Gay, 2009 [7]; 205; New Zealand; BF or cow’s milk | Meat Group: Red meat, 2 portions/d for 20wk (baseline 12-20mo) | SF: Meat, fortified milk groups (29ug/L, 95% CI: 1.02, 1.63; P=0.033, 1.68ug/L, 95% CI: 1.27, 2.24; P<0.001) vs. non-fortified milk group
Szymlek-Gay, 2009 [7]; 205; New Zealand; BF or cow’s milk | Fortified Milk Group: Replaced cow’s milk with iron-fortified powdered cow’s milk | Body iron: Fortified milk group (1.9mg/kg, 95% CI: 0.8, 3.1; P<0.001) vs. non-fortified milk group
Szymlek-Gay, 2009 [7]; 205; New Zealand; BF or cow’s milk | Non-Fortified Milk Group: Replaced regular cow’s milk with non-fortified powdered cow milk, | Hb, TfR, depleted iron stores, iron-deficient erythropoiesis, IDA: No significant group differences
Virtanen, 2001 [9]; 36; Sweden; BF and/or FF | Cow’s Milk, Low-Fat Group: Low-fat cow’s milk, ad libitum for 7mo (11 to 18mo) | Hb, MCV, SF, TfR from 12 to 18 mo: No significant group differences
Virtanen, 2001 [9]; 36; Sweden; BF and/or FF | Cow’s Milk, Standard-Fat Group: Standard-fat cow’s milk, ad libitum for 7mo (11 to 18mo)
Virtanen, 2001 [9]; 36; Sweden; BF and/or FF | Fortified Cow’s Milk, 50% Vegetable Fat Group: Iron-fortified cow’s milk with 50% vegetable fat, ad libitum for 7mo (11 to 18mo)
Virtanen, 2001 [9]; 36; Sweden; BF and/or FF | Fortified Cow’s Milk, 100% Vegetable Fat Group: Iron-fortified cow’s milk with 100% vegetable fat, ad libitum for 7mo (11 to 18mo)
Zavaleta, 2011 [26]; 499; Peru; Exclusively BF | Intervention Group: CFB with milkfat globule membrane and iron, zinc, copper, folate, thiamin, riboflavin, vitamin A, vitamin B12, and ascorbic acid for 6mo (from 6 to 12mo) | Hb at 12mo: 109.9 vs 108.1 vs. 109.9g/L; P=0.049 | Serum zinc, zinc deficiency (zinc <10.7umol/L) at 12mo: No significant group differences | Serum folate, folate deficiency (folate<6.8mg/nL) at 12mo: No significant group differences
Zavaleta, 2011 [26]; 499; Peru; Exclusively BF | Control Group: CFB with skim milk proteins and iron, zinc, copper, folate, thiamin, riboflavin, vitamin A, vitamin B12, and ascorbic acid) for 6mo | SF, anemia (Hb<11g/dL), IDA (SF<10ug/L) at 12mo: No significant group differences
Observational Studies
Dagnelie, 1994 [4]; Prospective Cohort Study; 106; The Netherlands | Macrobiotic weaning diet: Unpolished rice, pulses, vegetables, seaweeds, fermented foods, nuts, seeds, and no vitamin D supplements, fat/oils, fish and animal products | MCHC: Macrobiotic > omnivorous; P<0.05 | | Vitamin B12: Macrobiotic < omnivorous; P<0.001 | Vitamin D: Macrobiotic < omnivorous; P<0.001
Dagnelie, 1994 [4]; Prospective Cohort Study; 106; The Netherlands | Omnivorous weaning diet: Not described | Hct, RBX, MCV, MCH: Macrobiotic < omnivorous; P<0.04, P<0.001, P<0.05, P<0.001 | | Folate: Macrobiotic < omnivorous; P<0.001 | Rickets (total, subclinical, clinical): Macrobiotic > omnivorous; P<0.001
Dagnelie, 1994 [4]; Prospective Cohort Study; 106; The Netherlands | | Hb, FEP, SF: No significant associations
Male, 2001 [6]; Prospective Cohort Study; 488; Austria, Germany, Greece, Hungary, Ireland, Italy, Portugal, Spain, Sweden | Frequency of fruit and vegetable consumption: Never, 1–2 times/wk, weekly, almost daily from 9 to 12mo | Hb, MCV, SF, TSAT, TfR, anemia, ID, IDA: No significant associations
Michaelsen, 1995 [19]; Prospective Cohort Study; 84; Denmark | Amount of fish, bread, vegetables and fruits, other foods consumed: 100g/d | SF from 6 to 9mo: −2.68 (SD=0.71), P=0.001 for bread
| | SF from 6 to 9mo: No significant associations with fish, vegetables, fruits, “other foods”
Thorsdottir, 2003 [1]; Prospective Cohort Study; 114; Iceland | Amount of cow’s milk products, fish, fruit and vegetables, bread, biscuits and crackers, cakes, butter/cheese, juices consumed: g/d, 100g/d for juices from 9 to 12mo | SF at 12mo: 0.007 (SD=0.003), P=0.009 for fish; −0.009 (SD=0.004), P=0.042 for butter/cheese
Thorsdottir, 2003 [1]; Prospective Cohort Study; 114; Iceland | | Hb at 12mo: −0.285 (SD=0.124), P= 0.024 for butter/cheese
Thorsdottir, 2003 [1]; Prospective Cohort Study; 114; Iceland | | MCV at 12mo: 0.189 (SD=0.061), P= 0.002 for butter/cheese
Thorsdottir, 2003 [1]; Prospective Cohort Study; 114; Iceland | | TfR, TfR:log SF at 12mo: No significant associations
Tantrecheewathorn, 2005 [27]; Prospective Cohort Study; 140; Thailand | Dietary inadequacy vs. adequacy from 4-12mo, defined as a variety of food from various food groups (rice and grains, fruits, vegetables, milk, meat, eggs, fat), and adequate amounts of nutrients and energy compared with Thai Recommended Dietary Allowances | IDA at 12mo: RR=11.1, 95% CI: 4, 33.3; P<0.001

Table 4 Description of studies examined the relationship between types and amounts of complementary foods and beverages varied in fat content and micronutrient status

Reference; n; country; milk feeding practices | Intervention | Results for micronutrient and fatty acid status
Hoffman, 2004 [28]; RCT; 51; US; Exclusively BF | DHA Group: CFB enriched with DHA from egg-yolk for 6mo (from 6 to 12mo) | DHA, DPA (n-6), DHA/DPA(n-6), n-6/n-3 at 12mo: DHA > control group; P<0.002
Hoffman, 2004 [28]; RCT; 51; US; Exclusively BF | Control Group: Unenriched CFB for 6mo (from 6 to 12mo) | Hb, Hct, MCV, alpha-LNA, EPA, DPA (n-3), LA, 20:3, ARA, 22:4 at 12mo: No significant group differences
Libuda, 2015 [29]; RCT; 158; Germany; BF and/or FF | Rapeseed Oil Group: CFB meals with ALA-rich rapeseed oil for 4-6mo (from 4-6 to 10mo) | DHA, EPA, n3 LC-PUFA, n3 PUFA, n3 LC-PUFA:n6 LC-PUFA, n2 PUFA:n6 PUFA, ALA:LA, EPA:AA at 10mo: Fish > corn oil group; P=0.0001 (P=0.0002 for n3 PUFA, P=0.038 for ALA:LA)
Libuda, 2015 [29]; RCT; 158; Germany; BF and/or FF | Fish Group: CFB meals with salmon (preformed DHA) for 4-6mo (from 4-6 to 10mo) | DHA, EPA, AA, LA, n3 LC PUFA, n3 PUDA, n3 LC-PUFA: n6 LC-PFA, n3 PUFA: n6 PUFA, EPA:AA at 10mo: No significant differences between the rapeseed and corn oil groups
Libuda, 2015 [29]; RCT; 158; Germany; BF and/or FF | Corn Oil Group: CFB meals with linoleic acid-rich corn oil for 4-6mo (from 4-6 to 10mo) | ALA, ALA:LA at 10mo: Rapeseed > corn oil group; P=0.0001
Libuda, 2015 [29]; RCT; 158; Germany; BF and/or FF | | LA, AA, ALA at 10mo: No significant differences between the fish and corn oil groups
Makrides, 2002 [25]; RCT; 137; Australia; BF and/or FF | Regular Egg Group: Regular eggs, 4 yolks/wk for 6mo (from 6 to 12mo) | DHA at 12mo for BF infants: 6.7±0.1.3 vs 5.1±0.9, 4.8±0.8; P<0.05)
Makrides, 2002 [25]; RCT; 137; Australia; BF and/or FF | N-3 Egg Group: Eggs enriched with DHA, 4 yolks/wk for 6mo (from 6 to 12mo) | DHA at 12mo for FF infants: 4.1±0.1.2 vs 3.3±0.7,3.0±0.5; P<0.05
Makrides, 2002 [25]; RCT; 137; Australia; BF and/or FF | Control group: No intervention | AA at 12mo: No significant group differences
Schwartz, 2009 [30]; RCT; 102; Germany; Exclusively BF | Intervention Group: CFB meals with rapeseed (canola) oil (LA 20%; ALA 9%) for 4mo (from 6 to 10mo) | n-3 fatty acids, EPA, DHA at 10mo: Intervention > control; P<0.001, P<0.001, P=0.0157
Schwartz, 2009 [30]; RCT; 102; Germany; Exclusively BF | Control Group: CFB meals with corn oil (LA 55% of total fatty acid; ALA 1%) for 4mo (from 6 to 10mo) | Control vs. intervention group had higher n-6 fatty acids, LA, n-6/n-3, n-6/n-3 LCPUFA, AA/EPA, LA/ALA at 10mo: Control > intervention; P=0.0012, P=0.0002, P<0.001, P=0.0130, P<0.001, P=0.011
Schwartz, 2009 [30]; RCT; 102; Germany; Exclusively BF | | GLA, ALA, or AA at 10mo: No significant group differences
Svahn, 2002 [31]; RCT; 37; Sweden | Low-Fat Milk Group: Low-fat cow’s milk (1.0g fat/dL) for 3mo (from 12 to 15mo) | Plasma LA at 15mo: Full vegetable fat > low-fat, standard-fat groups; P<0.001
Svahn, 2002 [31]; RCT; 37; Sweden | Standard-Fat Milk Group: Standard fat cow’s milk (3.5g fat/dL) for 3mo (from 12 to 15mo) | Plasma ALA at 15mo: Partial vegetable > low-fat, standard-fat groups; Standard fat: P<0.001 in TG, P<0.05 in CE; Low-fat: P<0.01 in phospholipids and CE, P<0.05 in TG
Svahn, 2002 [31]; RCT; 37; Sweden | Partially Vegetable Fat Milk Group: Milk with 50% vegetable fat from rapeseed oil, 50% milk fat for 3mo (from 12 to 15mo) | Trans FA at 15mo: Partial, full vegetable fat < standard-fat group; SF vs PVF: P<0.05; SF vs FVF: P<0.01
Svahn, 2002 [31]; RCT; 37; Sweden | Full Vegetable Fat Milk Group: Milk with 100% vegetable fat from palm-, coconut- and soybean oil for 3mo (from 12 to 15mo) | Plasma AA or DHA in CE and PL: No significant group differences

### Included articles

1 Thorsdottir, I., ., Iron status at 12 months of age -- effects of body size, growth and diet in a population with high birth weight. Eur J Clin Nutr, 2003. 57(4): p. 505–13.12700611
2 Urkin, ., Indices of iron deficiency and anaemia in Bedouin and Jewish toddlers in southern Israel. Acta Paediatr, 2007. 96(6): p. 857–60.17465987
3 United Nations Development Programme, Human Development Report 2014. Sustaining Human Progress: Reducing Vulnerabilities and Building Resilience. 2014: New York.
4 Dagnelie, ., Macrobiotic nutrition and child health: results of a population-based, mixed-longitudinal cohort study in The Netherlands. Am J Clin Nutr, 1994. 59(5 Suppl): p. 1187s–1196s.8172122
5 Freeman, ., A longitudinal study of iron status in children at 12, 24 and 36 months. Public Health Nutr, 1998. 1(2): p. 93–100.10933405
6 Male, ., Prevalence of iron deficiency in 12-mo-old infants from 11 European areas and influence of dietary factors on iron status (Euro-Growth study). Acta Paediatr, 2001. 90(5): p. 492–8.11430706
7 Szymlek-Gay, E.A., ., Food-based strategies improve iron status in toddlers: a randomized controlled trial12. Am J Clin Nutr, 2009. 90(6): p. 1541–51.19828711
8 Taylor, ., Influence of diet on iron, copper, and zinc status in children under 24 months of age. Biol Trace Elem Res, 2004. 97(3): p. 197–214.14997021
9 Virtanen, M.A., ., Iron-fortified and unfortified cow’s milk: effects on iron intakes and iron status in young children. Acta Paediatr, 2001. 90(7): p. 724–31.11519973
10 Ziegler, E.E., S.E. Nelson, and J.M. Jeter, Iron status of breastfed infants is improved equally by medicinal iron and iron-fortified cereal. Am J Clin Nutr, 2009. 90(1): p. 76–87.19458014
11 Hertrampf, ., Haemoglobin fortified cereal: a source of available iron to breast-fed infants. Eur J Clin Nutr, 1990. 44(11): p. 793–8.2086208
12 Dube, ., Complementary food with low (8%) or high (12%) meat content as source of dietary iron: a double-blinded randomized controlled trial. Eur J Nutr, 2010. 49(1): p. 11–8.19618230
13 Engelmann, ., Meat intake and iron status in late infancy: an intervention study. J Pediatr Gastroenterol Nutr, 1998. 26(1): p. 26–33.9443116
14 Krebs, ., Effects of different complementary feeding regimens on iron status and enteric microbiota in breastfed infants. J Pediatr, 2013. 163(2): p. 416–23.23452586
15 Krebs, ., Meat as a first complementary food for breastfed infants: feasibility and impact on zinc intake and status. J Pediatr Gastroenterol Nutr, 2006. 42(2): p. 207–14.16456417
16 Krebs, ., Comparison of complementary feeding strategies to meet zinc requirements of older breastfed infants. Am J Clin Nutr, 2012. 96(1): p. 30–5.22648720
17 Makrides, ., A randomized controlled clinical trial of increased dietary iron in breast-fed infants. J Pediatr, 1998. 133(4): p. 559–62.9787699
18 Yeung, ., Efficacy of meat and iron-fortified commercial cereal to prevent iron depletion in cow milk-fed infants 6 to 12 months of age: a randomized controlled trial. Can J Public Health, 2000. 91(4): p. 263–7.10986782
19 Michaelsen, ., A longitudinal study of iron status in healthy Danish infants: effects of early iron status, growth velocity and dietary factors. Acta Paediatr, 1995. 84(9): p. 1035–44.8652956
20 Olaya, ., Efficacy and safety of new complementary feeding guidelines with an emphasis on red meat consumption: a randomized trial in Bogota, Colombia. Am J Clin Nutr, 2013. 98(4): p. 983–93.23945724
21 Davidsson, ., Dietary fiber in weaning cereals: a study of the effect on stool characteristics and absorption of energy, nitrogen, and minerals in healthy infants. J Pediatr Gastroenterol Nutr, 1996. 22(2): p. 167–79.8642490
22 Lind, ., Effects of weaning cereals with different phytate contents on hemoglobin, iron stores, and serum zinc: a randomized intervention in infants from 6 to 12 mo of age. Am J Clin Nutr, 2003. 78(1): p. 168–75.12816787
23 Walter, ., Effectiveness of iron-fortified infant cereal in prevention of iron deficiency anemia. Pediatrics, 1993. 91(5): p. 976–82.8474819
24 Liu, ., Nutritional efficacy of a fortified weaning rusk in a rural area near Beijing. Am J Clin Nutr, 1993. 57(4): p. 506–11.8460605
25 Makrides, ., Nutritional effect of including egg yolk in the weaning diet of breast-fed and formula-fed infants: a randomized controlled trial. Am J Clin Nutr, 2002. 75(6): p. 1084–92.12036817
26 Zavaleta, ., Efficacy of an MFGM-enriched complementary food in diarrhea, anemia, and micronutrient status in infants. J Pediatr Gastroenterol Nutr, 2011. 53(5): p. 561–8.21637131
27 Tantracheewathorn, ., Incidence and risk factors of iron deficiency anemia in term infants. J Med Assoc Thai, 2005. 88(1): p. 45–51.15960216
28 Hoffman, ., Maturation of visual acuity is accelerated in breast-fed term infants fed baby food containing DHA-enriched egg yolk. J Nutr, 2004. 134(9): p. 2307–13.15333721
29 Libuda, ., Fatty acid supply with complementary foods and LC-PUFA status in healthy infants: results of a randomised controlled trial. Eur J Nutr, 2015.
30 Schwartz, ., Modification of dietary polyunsaturated fatty acids via complementary food enhances n-3 long-chain polyunsaturated fatty acid synthesis in healthy infants: a double blinded randomised controlled trial. Arch Dis Child, 2009. 94(11): p. 876–82.19193660
31 Svahn, ., Different quantities and quality of fat in milk products given to young children: effects on long chain polyunsaturated fatty acids and trans fatty acids in plasma. Acta Paediatr, 2002. 91(1): p. 20–9.11885548

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. This is the analytic framework for the systematic review conducted to examine the relationship between types and amounts of complementary foods and beverages and micronutrient status.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts all contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on the timing of introduction of CFB and micronutrient status. For this systematic review, the target population considered was generally healthy infants fed humna milk, infant formula, or both, who had micronutrient status measured through age 24 months. The interventions or exposures considered were the types and/or amounts of CFB and their comparators were different types and amounts of CFB. Complementary feeding is defined as the process that starts when human milk or infant formula is complemented by other foods and beverages. The complementary feeding period typically continues to 24 months as the young child transitions fully to family foods.Complementary foods and beverages (CFB) are foods and beverages (liquids, semisolids, and solids) other than human milk or infant formula, provided to an infant or young child to provide nutrients and energy. The outcomes considered were iron, zinc, vitamin D, vitamin B12, folate, and/or fatty acid status. The key confounders were education, socioeconomic status, sex, maternal age, race and/or ethnicity, milk feeding practices (breast milk, infant formula, or both), birth size, and gestational age.

## SEARCH PLAN AND RESULTS

### Inclusion and exclusion criteria

The inclusion and exclusion criteria are a set of characteristics to determine which studies will be included or excluded in the systematic review. This table provides the inclusion and exclusion criteria for the systematic review question: What is the relationship between types and amounts of complementary foods and beverages and micronutrient status?

Table 5 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | Randomized controlled trials | Cross-sectional studies
Study design | Non-randomized controlled trials | Uncontrolled studies
Study design | Prospective cohort studies | Pre/post studies without a control
Study design | Retrospective cohort studies | Narrative reviews
Study design | Case-control studies | Systematic reviews
Study design | Pre/post studies with a control | Meta-analyses
Independent variable (intervention or exposure) | Types and amounts of complementary foods and beverages (i.e., foods and beverages other than human milk or infant formula (liquids, semisolids, and solids) provided to an infant or young child to provide nutrients and energy) | Consumption of fluid cow’s milk before 12 months of age
Comparator | Different types and amounts of CFB | N/A
Dependent variables (outcomes) | Iron status, including incidence of iron deficiency and anemia | N/A
| Zinc status
| Vitamin D status
| Vitamin B12 status
| Folate status
| Fatty acid status
Date range | January 1980 - March 2016
Language | Studies published in English | Studies published in languages other than English
Publication status | Studies published in peer-reviewed journals | Grey literature, including unpublished data, manuscripts, reports, abstracts, conference proceedings
Country^1,^ ^2,^ ^3^ | Studies conducted in Very High or High Human Development Countries | Studies conducted in Medium or Low Human Development Countries
Study participants | Human subjects | Hospitalized patients, not including birth and immediate post-partum hospitalization of healthy babies
Study participants | Males
Study participants | Females
Age of study participants | Age at intervention or exposure: Infants (0-12mo); Toddlers (12-24mo) | Age at intervention or exposure: Child (2-5 years (y)); Child (6-12y); Adolescents (13-18y); Adults (19y and older); Older adults (65 to 79y); Older adults (80+y)
Age of study participants | Age at outcome: Infants (0-12mo); Toddlers (12-24mo) | Age at outcome: Child (2-5y); Child (6-12y); Adolescents (13-18y); Adults (19y and older); Older adults (65 to 79y); Older adults (80+y)
Health status of study participants | Studies done in generally healthy populations | Studies that exclusively enroll subjects with a disease or with the health outcome of interest
Health status of study participants | Studies done in populations where infants were full term (≥37wk gestational age) | Studies done in hospitalized or malnourished subjects
Health status of study participants | Studies done in populations with elevated chronic disease risk, or that enroll some participants with a disease or with the health outcome of interest | Studies of exclusively pre-term babies (gestational age <37wk) or babies that are small for gestational age (<2500g)
Health status of study participants | | Studies of subjects with infectious diseases (e.g. HIV/AIDS) (or with mothers diagnosed with an infectious disease)

1 United Nations Development Programme. Human Development Report 2014: Reducing Vulnerabilities and Building Resilience. Available from: http://hdr.undp.org/en/content/human-development-report-2014 .[3]

2 Medium Development countries were originally included, but due to concerns about generalizability to the U.S. of study participants (i.e., baseline health status) and complementary foods and beverages typically consumed, a decision was made to exclude “Medium” countries in October 2017.

3 When a country was not included in the HDI ranking, country classification from the World Bank was used instead [32]

### Search terms and electronic databases used

#### PubMed, US National Library of Medicine (https://www.nlm.nih.gov/bsd/medline.html) (1966 to 9 March 2016)

Date(s) Searched: 12/9/2015; 3/9/2016

Search Terms:

((Complementary OR supplementary OR wean* OR transition* OR introduc* OR “Infant Nutritional Physiological Phenomena”[Mesh:noexp] OR weaning[mesh])

AND (feeding* OR food* OR beverage*[tiab] OR beverages[mh] OR eating OR diet[tiab] OR diet[mh] OR meal*[tiab] OR meals[mh] OR “Food and Beverages”[Mesh] OR diets[tiab] OR cereal*[tiab] OR “Edible Grain”[Mesh] OR bread*[tiab] OR whole grain* OR juice*[tiab] OR milk[tiab] OR “Milk”[Mesh] OR dairy[tiab] OR “Dairy Products”[Mesh] OR meat[tiab] OR cheese[tiab] OR yogurt[tiab] OR yoghurt*[tiab] OR fruit*[tiab] OR “Fruit”[Mesh] OR vegetable*[tiab] OR “Vegetables”[Mesh] OR egg*[tiab] OR “Eggs”[Mesh] OR nut[tiab] OR nuts[tiab] OR peas[tiab] OR beans[tiab] OR legume*[tiab] OR snack*[tiab])) OR “infant food”[mesh]

AND

nutritional status[mh] OR nutritional status*[tiab] OR Nutrition Status*[tiab] OR “Nutritional Requirements”[Mesh] OR Iron[mh] OR iron[tiab] OR “Anemia”[Mesh] OR “Anemia”[tiab] OR iron deficien*[tiab] OR ferritin*[tiab] OR ferrous[tiab] OR “Transferrin”[Mesh] OR “Transferrin”[tiab] OR zinc OR “Vitamin D”[Mesh] OR “Vitamin D”[tiab] OR “Vitamin D Deficiency”[Mesh] OR “Vitamin B 12”[Mesh] OR “Vitamin B 12”[tiab] OR “Vitamin B12”[tiab] OR “Vitamin B 12 Deficiency”[Mesh] OR Cobamide*[tiab] OR Cobalamin*[tiab] OR Cyanocobalamin[tiab] OR Folate[tiab] OR “Folic Acid”[Mesh] OR folacin[tiab] OR vitamin b9*[tiab] OR Fatty acid*[tiab] OR “Fatty Acids”[Mesh:noexp] OR fatty acid*[tiab] OR “Fatty Acids, Unsaturated”[Mesh:noexp] OR Arachidonic acid*[tiab] OR linolenic acid*[tiab] OR linoleic acid*[tiab] OR Docosahexaenoic Acid*[tiab] OR Eicosapentaenoic Acid*[tiab] OR gamma-Linolenic Acid*[tiab] OR “Arachidonic Acids”[Mesh] OR “Fatty Acids, Essential”[Mesh] OR “Fatty Acids, Omega-3”[Mesh] OR “Fatty Acids, Omega-6”[Mesh] OR alpha-Linolenic Acid*[tiab] OR “Fatty Acids, Essential”[Mesh] OR “Linolenic Acids”[Mesh] OR “Trans Fatty Acids”[Mesh] OR “Fatty Acids, Monounsaturated”[Mesh] 905815

NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic[sb])

OR ((Solid food*) OR solids)); AND

OR

Nutrition*[ti] OR nutritional status[mh] OR nutritional status*[tiab] OR Nutrition Status*[tiab] OR “Child Nutrition Sciences”[majr] OR nutrient*[ti] OR “Nutritional Requirements”[Mesh]

“Vitamin B Deficiency”[Mesh] OR “Vitamins”[Mesh] OR Iron[mh] OR iron[tiab] OR “Anemia”[Mesh] OR “Anemia”[tiab] OR iron deficien*[tiab] OR ferritin*[tiab] OR ferrous[tiab] OR “Transferrin”[Mesh] OR “Transferrin”[tiab] OR zinc OR “Vitamin D”[Mesh] OR “Vitamin D”[tiab] OR “Vitamin D Deficiency”[Mesh] OR “Vitamin B 12”[Mesh] OR “Vitamin B 12”[tiab] OR “Vitamin B12”[tiab] OR “Vitamin B 12 Deficiency”[Mesh] OR Cobamide*[tiab] OR Cobalamin*[tiab] OR Cyanocobalamin[tiab] OR Folate[tiab] OR “Folic Acid”[Mesh] OR folacin[tiab] OR vitamin b9*[tiab] OR Fatty acid*[tiab] OR “Fatty Acids”[Mesh:noexp] OR fatty acid*[tiab] OR “Fatty Acids, Unsaturated”[Mesh:noexp] OR Arachidonic acid*[tiab] OR linolenic acid*[tiab] OR linoleic acid*[tiab] OR Docosahexaenoic Acid*[tiab] OR Eicosapentaenoic Acid*[tiab] OR gamma-Linolenic Acid*[tiab] OR “Arachidonic Acids”[Mesh] OR “Fatty Acids, Essential”[Mesh] OR “Fatty Acids, Omega-3”[Mesh] OR “Fatty Acids, Omega-6”[Mesh] OR alpha-Linolenic Acid*[tiab] OR “Fatty Acids, Essential”[Mesh] OR “Linolenic Acids”[Mesh] OR “Trans Fatty Acids”[Mesh] OR “Fatty Acids, Monounsaturated”[Mesh]

AND

infant* OR baby OR babies OR toddler* OR newborn*[tiab] OR “Child, Preschool”[Mesh] OR preschool*[tiab] OR pre-school*[tiab] OR “early childhood”[tiab] OR “early years”[tiab] OR pre-k[tiab] OR pre-primary[tiab] OR under five*[ti] OR young child*[ti] OR “head start”[tiab] OR prekindergarten[tiab] OR pre-kindergarten[tiab] OR weanling*

OR limit to child, preschool in PubMed?

NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic[sb])

#### Embase, Elsevier (https://www.elsevier.com/solutions/embase-biomedical-research/embase-coverage-and-content) (1947 to 9 December 2015)

Date(s) Searched: 12/9/2015

Search Terms:

(Complementary OR supplementa* OR wean* OR transition* OR introduc* OR family) NEAR/3 (feed* OR food* OR beverage* OR eating OR diet)

OR

(Complementary OR transition* OR introduct* OR wean*) AND (food/exp OR ‘baby food’/exp OR ‘cereal’/exp OR ‘dairy product’/exp OR ‘egg’/exp OR ‘fruit’/exp OR ‘meat’/exp OR ‘sea food’/exp OR ‘milk’/exp OR fish/exp OR ‘poultry’/exp OR ‘beverage’/exp OR ‘vegetable’/exp OR nut/exp OR pea/exp OR meal/exp)

OR

(Complementary OR supplementa* OR wean* OR transition* OR introduc*) NEAR/5 (‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR beverage* OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR bread* OR yog*urt* OR cheese* OR juice* OR rice OR soup OR legume* OR snack* OR meal*) (for Embase)

AND

(infant*:ti,ab OR infant/exp) OR (baby OR babies OR toddler* OR newborn* OR nurser*):ti,ab OR ‘newborn’/exp OR ‘newborn care’/exp OR preschool*:ti,ab OR pre-school:ti,ab OR ‘preschool child’/exp OR ‘infancy’/exp OR “early childhood”:ti,ab OR “early years” OR pre-k:ti,ab OR ‘nursery’/exp OR ‘nursery school’/exp OR prekindergarten:ti,ab OR pre-kindergarten:ti,ab OR weanling*

AND ([in process]/lim OR [article]/lim OR [article in press]/lim) AND ([embase]/lim NOT [medline]/lim)

AND

Limit to humans

OR

‘nutritional status’/exp OR ((nutrition* OR diet) NEAR/3 (status OR requirement* OR state)):ti,ab OR ‘nutritional requirement’/exp

OR

‘ferrous ion’/exp OR ferrous:ti,ab OR ‘iron absorption’/exp OR ‘iron deficiency anemia’/exp OR anemia:ti,ab OR ‘iron blood level’/exp OR ‘iron’/exp OR ‘ferritin’/exp OR ferritin:ti,ab OR transferrin:ti,ab OR ‘transferrin’/exp OR ‘vitamin D’/exp OR ‘vitamin D deficiency’/exp OR ‘zinc’/exp OR zinc:ti,ab OR ‘cyanocobalamin’/exp OR “vitamin d”:ti,ab OR “vitamin b12”:ti,ab OR “vitamin b 12”:ti,ab OR cyanocobalamin:ti,ab OR ‘folic acid’/exp OR ‘folic acid’:ti,ab OR folate:ti,ab OR folacin:ti,ab OR ‘cobalamin’/exp OR cobalamin*:ti,ab OR ‘cobamamide’/exp OR ‘cobamamide’:ti,ab OR cyanocobalamin*:ti,ab OR ‘fatty acid’/exp OR (fatty NEXT/1 acid*):ti,ab OR (Arachidonic acid*):ti,ab OR (linolenic NEXT/1 acid*):ti,ab OR (linoleic NEXT/1 acid*):ti,ab OR (Docosahexaenoic NEXT/1 Acid*):ti,ab OR (Eicosapentaenoic NEXT/1 Acid*):ti,ab OR (gamma-Linolenic NEXT/1 Acid*):ti,ab OR (alpha-Linolenic NEXT/1 Acid*):ti,ab

#### Cochrane Central Register of Controlled Trials (https://handbook-5-1.cochrane.org/chapter_6/6_2_1_2_the_cochrane_central_register_of_controlled_trials.htm), John Wiley & Sons in the Cochrane Library (searched August 2015)

Date(s) Searched: 12/2015

Search Terms:

(feed* OR food* OR beverage*OR diet* OR ‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR nut OR cereal OR beverage* OR bread* OR seafood OR yog*urt* OR cheese OR juice) NEAR/3 (Complementary OR supplementa* OR wean* OR transition* OR introduct* OR family)

OR

((nutrition* OR diet) NEAR/3 (status OR requirement* OR state))

AND

ferrous OR iron OR anemia OR ferritin OR zinc OR “vitamin d” OR “vitamin b12” OR “vitamin b 12” OR cyanocobalamin OR ‘folic acid’ OR folate OR folacin OR cobalamin* OR ‘cobamamide’ OR cyanocobalamin* OR (fatty NEXT/1 acid*) OR (Arachidonic acid*) OR (linolenic NEXT/1 acid*) OR (linoleic NEXT/1 acid*) OR (Docosahexaenoic NEXT/1 Acid*) OR (Eicosapentaenoic NEXT/1 Acid*) OR (gamma-Linolenic NEXT/1 Acid*) OR (alpha-Linolenic NEXT/1 Acid*)

NOT (supplement*ti,ab OR pubmed OR embase)

AND (infant* OR baby OR babies OR toddler* OR newborn* OR nurser* OR preschool* OR pre-school OR “early childhood” OR pre-k OR prekindergarten OR pre-kindergarten OR “early years”)

NOT (pubmed OR embase OR supplement*:ti OR preterm:ti)

#### CINAHL Plus with Full Text, EBSCO (https://www.ebsco.com/products/research-databases/cinahl-plus-full-text) (Cumulative Index to Nursing and Allied Health Literature; 1937 to 14 December 2015)

Date(s) Searched: 12/14/2015

Search Terms:

(MH “Food and Beverages+”) OR (MH “Food”) OR (MH “Diet”) OR (MH “Eating”) OR (MH “Eating Behavior”) OR (MH “Taste”) OR (MH “Taste Buds”) OR (MH “Cereals”) OR (MH “Dairy Products”) OR (MH “Yogurt”) OR (MH “Cheese”) OR (MH “Milk”) OR (MH “Eggs”) OR (MH “Fruit”) OR (MH “Fruit Juices”) OR (MH “Meat”) OR (MH “Seafood”) OR (MH “Fish”) OR (MH “Poultry”) OR (MH “Vegetables”) OR (MH “Nuts”) OR (MH “Legumes”) OR (MH “Bread”) AND (Complementary OR supplementa* OR wean* OR transition* OR introduc*)

OR

(‘whole grain’ OR ‘whole grains’ OR dairy OR egg OR eggs OR meat OR poultry OR seafood OR fruit* OR milk OR fish* OR poultry OR vegetables* OR pea OR peas OR nut OR nuts OR cereal OR beverage* OR bread* OR seafood OR yog*urt* OR cheese* OR juice*) N5 (Complementary OR supplementa* OR wean* OR transition* OR introduc* OR family)

AND

(MH “Nutritional Status”) OR “nutritional status” OR (MH “Nutritional Requirements”) OR (MH “Vitamin D”) OR (MH “Vitamin D Deficiency”) OR (MH “Vitamin B12 Deficiency”) OR (MH “Anemia”) OR “anemia” OR (MH “Anemia, Iron Deficiency”) OR (MH “Iron”) OR (MH “Zinc”) OR (MH “Vitamin B12”) OR (MH “Vitamin B12 Deficiency”) OR (MH “Folic Acid”) OR (MH “Niacin”) OR (MH “Folic Acid Deficiency”) OR “folate” OR “folacin” OR cyanocobalamin* OR cobalamin* OR cobamamide* OR (MH “Fatty Acids”) OR “fatty acids” OR (MH “Fatty Acids, Omega-6”) OR (MH “Fatty Acids, Omega-3”) OR (MH “Fatty Acids, Unsaturated”) OR (MH “Trans Fatty Acids”) OR (MH “Fatty Acids, Monounsaturated”) OR (MH “Fatty Acids, Saturated”) OR (MH “Fatty Acids, Essential”) OR (MH “Arachidonic Acids”) OR (MH “Docosahexaenoic Acids”) OR (MH “Linolenic Acids”) OR (MH “Linoleic Acids”)

Limit to “all infant” OR (MH “Infant”) OR (MH “Infant, Newborn”) OR (MH “Infant Behavior”) OR (MH “Infant Feeding”) OR (MH “Infant Feeding Schedules”) OR (MH “Child, Preschool”)

Figure 2 Flow chart of literature search and screening results

Flow chart of literature search and screening results for articles examining the relationship between complementary feeding and micronutrient status. The results of an electronic database search were screened in a dual, step-wise manner by reviewing titles, abstracts, and full text articles to determine which articles met the criteria for inclusion. A manual search was done to ascertain articles not identified through the electronic database search. The SR on timing of introduction of CFB included nine articles, and the SR on types and amounts of CFB consumed included 33 articles.

Flow chart of literature search and screening results for articles examining the relationship between complementary feeding and micronutrient status. The results of an electronic database search were screened in a dual, step-wise manner by reviewing titles, abstracts, and full text articles to determine which articles met the criteria for inclusion. A manual search was done to ascertain articles not identified through the electronic database search. The systematic review on timing of introduction of CFB included nine articles, and the systematic review on types and amounts of CFB consumed included 33 articles.

### Excluded articles

The table below lists the excluded articles with at least one reason for exclusion, and may not reflect all possible reasons.

Table 6 Excluded articles

| Citation | Rationale
1 | Bioavailability of milk zinc in infants. Nutr Rev. 1984;42:220-2. | Study design, Dependent variable
2 | Nutritional findings in the U.S. preschool and young school-age population. J Bergen Cty Dent Soc. 1984;50:14-6. | Age
3 | Aboud,F. E.,Moore,A. C.,Akhter,S.. Effectiveness of a community-based responsive feeding programme in rural Bangladesh: a cluster randomized field trial. Matern Child Nutr. 2008;4:275-86. | Independent variable, Dependent variable
4 | Abrams,S. A.,O’Brien,K. O.,Wen,J.,Liang,L. K.,Stuff,J. E.. Absorption by 1-year-old children of an iron supplement given with cow’s milk or juice. Pediatr Res. 1996;39:171-5. | Independent variable, Dependent variable
5 | Abrams,S. A.,Wen,J.,Stuff,J. E.. Absorption of calcium, zinc, and iron from breast milk by five- to seven-month-old infants. Pediatr Res. 1997;41:384-90. | Study design, Independent variable
6 | Adamska,I.,Światek,K.,Czerwionka-Szaflarska,M.,Zawadzka-Gralec,A.. Influence of elimination diet on nutritional assessment in children under the age of 2 years. Pediatria Wspolczesna. 2007;9:29-36. | Dependent variable, Language
7 | Adu-Afarwuah,S.,Lartey,A.,Brown,K. H.,Zlotkin,S.,Briend,A.,Dewey,K. G.. Home fortification of complementary foods with micronutrient supplements is well accepted and has positive effects on infant iron status in Ghana. Am J Clin Nutr. 2008;87:929-38. | Country, Independent variable
8 | Agarwal,R.,Virmani,D.,Jaipal,M.,Gupta,S.,Sankar,M. J.,Bhatia,S.,Agarwal,A.,Devgan,V.,Deorari,A.,Paul,V. K.,Toteja,G. S.. Poor zinc status in early infancy among both low and normal birth weight infants and their mothers in Delhi. Neonatology. 2013;103:54-9. | Country, Independent variable
9 | Agostoni,C.,Marangoni,F.,Giovannini,M.,Galli,C.,Riva,E.. Prolonged breast-feeding (six months or more) and milk fat content at six months are associated with higher developmental scores at one year of age within a breast-fed population. Adv Exp Med Biol. 2001;501:137-41. | Independent variable
10 | Agostoni,C.,Riva,E.. Dietary fatty acids and cholesterol in the first 2 years of life. Prostaglandins Leukot Essent Fatty Acids. 1998;58:33-7. | Study design
11 | Agostoni,C.,Trojan,S.,Bellu,R.,Riva,E.,Bruzzese,M. G.,Giovannini,M.. Developmental quotient at 24 months and fatty acid composition of diet in early infancy: a follow up study. Arch Dis Child. 1997;76:421-4. | Independent variable, Dependent variable
12 | Agustina,R.,Bovee-Oudenhoven,I. M.,Lukito,W.,Fahmida,U.,van de Rest,O.,Zimmermann,M. B.,Firmansyah,A.,Wulanti,R.,Albers,R.,van den Heuvel,E. G.,Kok,F. J.. Probiotics Lactobacillus reuteri DSM 17938 and Lactobacillus casei CRL 431 modestly increase growth, but not iron and zinc status, among Indonesian children aged 1-6 years. J Nutr. 2013;143:1184-93. | Age, Country, Independent variable
13 | Al-Alawi,M.,Sarhan,N.. Prevalence of anemia among nine-month-old infants attending primary care in Bahrain. Journal of the Bahrain Medical Society. 2014;25:29-32. | Study design, Independent variable
14 | Al-Atawi,M. S.,Al-Alwan,I. A.,Al-Mutair,A. N.,Tamim,H. M.,Al-Jurayyan,N. A.. Epidemiology of nutritional rickets in children. Saudi J Kidney Dis Transpl. 2009;20:260-5. | Study design, Independent variable
15 | Alexy,U.,Kersting,M.,Sichert-Hellert,W.,Manz,F.,Schoch,G.. Energy intake and growth of 3- to 36-month-old German infants and children. Ann Nutr Metab. 1998;42:68-74. | Independent variable, Dependent variable
16 | Almquist-Tangen,G.,Dahlgren,J.,Roswall,J.,Bergman,S.,Alm,B.. Milk cereal drink increases BMI risk at 12 and 18 months, but formula does not. Acta Paediatr. 2013;102:1174-9. | Dependent variable
17 | Almqvist,C.,Garden,F.,Xuan,W.,Mihrshahi,S.,Leeder,S. R.,Oddy,W.,Webb,K.,Marks,G. B.. Omega-3 and omega-6 fatty acid exposure from early life does not affect atopy and asthma at age 5 years. J Allergy Clin Immunol. 2007;119:1438-44. | Independent variable, Dependent variable
18 | Altucher,K.,Rasmussen,K. M.,Barden,E. M.,Habicht,J. P.. Predictors of improvement in hemoglobin concentration among toddlers enrolled in the Massachusetts WIC Program. J Am Diet Assoc. 2005;105:709-15. | Independent variable, Dependent variable
19 | Anand,K.,Lakshmy,R.,Janakarajan,V. N.,Ritvik,A.,Misra,P.,Pandey,R. M.,Kapoor,S. K.,Sankar,R.,Bulusu,S.. Effect of consumption of micronutrient fortified candies on the iron and vitamin A status of children aged 3-6 years in rural Haryana. Indian Pediatr. 2007;44:823-9. | Age, Independent variable
20 | Andersen,A. D.,Michaelsen,K. F.,Hellgren,L. I.,Trolle,E.,Lauritzen,L.. A randomized controlled intervention with fish oil versus sunflower oil from 9 to 18 months of age: exploring changes in growth and skinfold thicknesses. Pediatr Res. 2011;70:368-74. | Independent variable
21 | Andersen,L. B.,Pipper,C. B.,Trolle,E.,Bro,R.,Larnkjaer,A.,Carlsen,E. M.,Molgaard,C.,Michaelsen,K. F.. Maternal obesity and offspring dietary patterns at 9 months of age. Eur J Clin Nutr. 2015;69:668-75. | Dependent variable
22 | Anfield,L.. Nutrition in the first year. Midwife Health Visit Community Nurse. 1985;21:161-4. | Study design
23 | Antunes,H.,Santos,C.,Carvalho,S.,Gonçalves,S.,Costa-Pereira,A.. Male gender is an important clinical risk factor for iron deficiency in healthy infants. e-SPEN Journal. 2012;7:e219-e222. | Study design, Independent variable
24 | Arsenault,J. E.,Lopez de Romana,D.,Penny,M. E.,Van Loan,M. D.,Brown,K. H.. Additional zinc delivered in a liquid supplement, but not in a fortified porridge, increased fat-free mass accrual among young Peruvian children with mild-to-moderate stunting. J Nutr. 2008;138:108-14. | Health Status
25 | Arvas,A.,Elgormus,Y.,Gur,E.,Alikasifoglu,M.,Celebi,A.. Iron status in breast-fed full-term infants. Turk J Pediatr. 2000;42:22-6. | Independent variable
26 | Ayer,J. G.,Harmer,J. A.,Xuan,W.,Toelle,B.,Webb,K.,Almqvist,C.,Marks,G. B.,Celermajer,D. S.. Dietary supplementation with n-3 polyunsaturated fatty acids in early childhood: effects on blood pressure and arterial structure and function at age 8 y. Am J Clin Nutr. 2009;90:438-46. | Age
27 | Baatenburg de Jong,R.,Bekhof,J.,Roorda,R.,Zwart,P.. Severe nutritional vitamin deficiency in a breast-fed infant of a vegan mother. Eur J Pediatr. 2005;164:259-60. | Study design
28 | Bakker,E. C.,van Houwelingen,A. C.,Hornstra,G.. Early nutrition, essential fatty acid status and visual acuity of term infants at 7 months of age. Eur J Clin Nutr. 1999;53:872-9. | Study design
29 | Balogun,T. A.,Lombard,M. J.,McLachlan,M.. The nutrient intake of children aged 12-36 months living in two communities in the Breede Valley, Western Cape province, South Africa. South African Family Practice. 2015;57:1-7 7p. | Study design, Country
30 | Bamji,M. S.,Chowdhury,N.,Ramalakshmi,B. A.,Jacob,C. M.. Enzymatic evaluation of riboflavin status of infants. Eur J Clin Nutr. 1991;45:309-13. | Study design
31 | Baptist,E. C.,Castillo,S. F.. Cow’s milk-induced iron deficiency anemia as a cause of childhood stroke. Clin Pediatr (Phila). 2002;41:533-5. | Study design
32 | Begin,F.,Santizo,M. C.,Peerson,J. M.,Torun,B.,Brown,K. H.. Effects of bovine serum concentrate, with or without supplemental micronutrients, on the growth, morbidity, and micronutrient status of young children in a low-income, peri-urban Guatemalan community. Eur J Clin Nutr. 2008;62:39-50. | Independent variable
33 | Beinner,M. A.,Lamounier,J. A.,Tomaz,C.. Effect of iron-fortified drinking water of daycare facilities on the hemoglobin status of young children. J Am Coll Nutr. 2005;24:107-14. | Age, Independent variable
34 | Beinner,M. A.,Velasquez-Melendez,G.,Pessoa,M. C.,Greiner,T.. Iron-fortified rice is as efficacious as supplemental iron drops in infants and young children. J Nutr. 2010;140:49-53. | Health Status, Independent variable
35 | Ben,X. M.,Zhou,X. Y.,Zhao,W. H.,Yu,W. L.,Pan,W.,Zhang,W. L.,Wu,S. M.,Van Beusekom,C. M.,Schaafsma,A.. Growth and development of term infants fed with milk with long-chain polyunsaturated fatty acid supplementation. Chin Med J (Engl). 2004;117:1268-70. | Independent variable
36 | Bentley,M. E.,Caulfield,L. E.,Ram,M.,Santizo,M. C.,Hurtado,E.,Rivera,J. A.,Ruel,M. T.,Brown,K. H.. Zinc supplementation affects the activity patterns of rural Guatemalan infants. J Nutr. 1997;127:1333-8. | Independent variable
37 | Berger,J.,Ninh,N. X.,Khan,N. C.,Nhien,N. V.,Lien,D. K.,Trung,N. Q.,Khoi,H. H.. Efficacy of combined iron and zinc supplementation on micronutrient status and growth in Vietnamese infants. Eur J Clin Nutr. 2006;60:443-54. | Country, Independent variable
38 | Bernal,M. J.,Periago,M. J.,Martinez,R.,Ortuno,I.,Sanchez-Solis,M.,Ros,G.,Romero,F.,Abellan,P.. Effects of infant cereals with different carbohydrate profiles on colonic function--randomised and double-blind clinical trial in infants aged between 6 and 12 months--pilot study. Eur J Pediatr. 2013;172:1535-42. | Independent variable, Dependent variable
39 | Bilenko,N.,Fraser,D.,Vardy,H.,Belmaker,I.. Impact of multiple micronutrient supplementation (“sprinkles”) on iron deficiency anemia in Bedouin Arab and Jewish infants. Isr Med Assoc J. 2014;16:434-8. | Independent variable
40 | Birch,E. E.,Garfield,S.,Hoffman,D. R.,Uauy,R.,Birch,D. G.. A randomized controlled trial of early dietary supply of long-chain polyunsaturated fatty acids and mental development in term infants. Dev Med Child Neurol. 2000;42:174-81. | Independent variable
41 | Birch,E. E.,Hoffman,D. R.,Uauy,R.,Birch,D. G.,Prestidge,C.. Visual acuity and the essentiality of docosahexaenoic acid and arachidonic acid in the diet of term infants. Pediatr Res. 1998;44:201-9. | Independent variable
42 | Birkbeck,J. A.,Scott,H. F.. 25-Hydroxycholecalciferol serum levels in breast-fed infants. Arch Dis Child. 1980;55:691-5. | Independent variable
43 | Birlouez-Aragon,I.,Rivière,S.,Bailly,L.,Burban,Y.,Dardenne,A.,Pertuis,S.. Restoration of nutritional balance in children between 6 and 8 years of age. Journal de Pediatrie et de Puericulture. 1998;11:98-103. | Age, Language
44 | Black,A. P.,Vally,H.,Morris,P.,Daniel,M.,Esterman,A.,Smith,F.,O’Dea,K.. High folate levels in Aboriginal children after subsidised fruit and vegetables and mandatory folic acid fortification. Aust N Z J Public Health. 2014;38:241-6. | Study design, Age
45 | Block,S. L.. Delayed introduction of solid foods to infants: not so fast!. Pediatr Ann. 2013;42:143-7. | Study design
46 | Bloem,M. W.,Wedel,M.,Egger,R. J.,Speek,A. J.,Schrijver,J.,Saowakontha,S.,Schreurs,W. H.. Iron metabolism and vitamin A deficiency in children in northeast Thailand. Am J Clin Nutr. 1989;50:332-8. | Health Status
47 | Bogard,J. R.,Hother,A. L.,Saha,M.,Bose,S.,Kabir,H.,Marks,G. C.,Thilsted,S. H.. Inclusion of Small Indigenous Fish Improves Nutritional Quality During the First 1000 Days. Food Nutr Bull. 2015;36:276-89. | Dependent variable
48 | Bortolini,G. A.,Vitolo,M. R.. The impact of systematic dietary counseling during the first year of life on prevalence rates of anemia and iron deficiency at 12-16 months. J Pediatr (Rio J). 2012;88:33-9. | Independent variable
49 | Brady,H.,Lamb,M. M.,Sokol,R. J.,Ross,C. A.,Seifert,J. A.,Rewers,M. J.,Norris,J. M.. Plasma micronutrients are associated with dietary intake and environmental tobacco smoke exposure in a paediatric population. Public Health Nutr. 2007;10:712-8. | Age, Independent variable
50 | Briend,A.,Bari,A.. Breastfeeding improves survival, but not nutritional status, of 12-35 months old children in rural Bangladesh. Eur J Clin Nutr. 1989;43:603-8. | Country, Independent variable, Dependent variable
51 | Brito,A.,Olivares,M.,Pizarro,T.,Rodriguez,L.,Hertrampf,E.. Chilean complementary feeding program reduces anemia and improves iron status in children aged 11 to 18 months. Food Nutr Bull. 2013;34:378-85. | Study design
52 | Brooke,O. G.. Supplementary vitamin D in infancy and childhood. Arch Dis Child. 1983;58:573-4. | Study design
53 | Brown,K. H.,Lopez de Romana,D.,Arsenault,J. E.,Peerson,J. M.,Penny,M. E.. Comparison of the effects of zinc delivered in a fortified food or a liquid supplement on the growth, morbidity, and plasma zinc concentrations of young Peruvian children. Am J Clin Nutr. 2007;85:538-47. | Independent variable
54 | Brunskill,A. J.,Ng,K. T.. The prevalence of and antecedents to iron deficiency in infants in a Victorian shire. Community Health Stud. 1986;10:167-72. | Study design, Independent variable
55 | Brunt,Deborah R.,Grant,Cameron C.,Wall,Clare R.,Reed,Peter W.. Interaction between risk factors for iron deficiency in young children. Nutrition & Dietetics. 2012;69:285-292 8p. | Study design
56 | Calvo,E. B.,Galindo,A. C.,Aspres,N. B.. Iron status in exclusively breast-fed infants. Pediatrics. 1992;90:375-9. | Independent variable
57 | Calvo,E. B.,Gnazzo,N.. Prevalence of iron deficiency in children aged 9-24 mo from a large urban area of Argentina. Am J Clin Nutr. 1990;52:534-40. | Study design, Independent variable
58 | Calvo,E.,Hertrampf,E.,Pablo,S.,Amar,M.,Stekel,A.. Haemoglobin-fortified cereal: an alternative weaning food with high iron bioavailability. European journal of clinical nutrition. 1989;43:237-43. | Independent variable, Dependent variable
59 | Cameron,S. L.,Taylor,R. W.,Heath,A. L.. Development and pilot testing of Baby-Led Introduction to SolidS--a version of Baby-Led Weaning modified to address concerns about iron deficiency, growth faltering and choking. BMC Pediatr. 2015;15:99. | Independent variable, Dependent variable
60 | Capozzi,L.,Russo,R.,Bertocco,F.,Ferrara,D.,Ferrara,M.. Diet and iron deficiency in the first year of life: a retrospective study. Hematology. 2010;15:410-3. | Study design, Independent variable
61 | Capozzi,L.,Russo,R.,Bertocco,F.,Ferrara,D.,Ferrara,M.. Effect on haematological and anthropometric parameters of iron supplementation in the first 2 years of life. Risks and benefits. Hematology. 2011;16:261-4. | Independent variable
62 | Carruth,B. R.,Nevling,W.,Skinner,J. D.. Developmental and food profiles of infants born to adolescent and adult mothers. J Adolesc Health. 1997;20:434-41. | Independent variable, Dependent variable
63 | Chang,S.,Huang,Z.,Ma,Y.,Piao,J.,Yang,X.,Zeder,C.,Hurrell,R. F.,Egli,I.. Mixture of ferric sodium ethylenediaminetetraacetate (NaFeEDTA) and ferrous sulfate: an effective iron fortificant for complementary foods for young Chinese children. Food Nutr Bull. 2012;33:111-6. | Age
64 | Chang,Y.,Zhai,F.,Li,W.,Ge,K.,Jin,D.,de Onis,M.. Nutritional status of preschool children in poor rural areas of China. Bull World Health Organ. 1994;72:105-12. | Study design, Age
65 | Chavasit,V.,Porasuphatana,S.,Suthutvoravut,U.,Zeder,C.,Hurrell,R.. Iron bioavailability in 8-24-month-old Thai children from a micronutrient-fortified quick-cooking rice containing ferric ammonium citrate or a mixture of ferrous sulphate and ferric sodium ethylenediaminetetraacetic acid. Maternal and Child Nutrition. 2015. | Dependent variable
66 | Chawla,P.,Puri,R.. Impact of pre-school supplementary feeding on clinical picture. Indian Pediatr. 1983;20:507-12. | Study design, Age
67 | Chierici,R.,Sawatzki,G.,Tamisari,L.,Volpato,S.,Vigi,V.. Supplementation of an adapted formula with bovine lactoferrin. 2. Effects on serum iron, ferritin and zinc levels. Acta Paediatr. 1992;81:475-9. | Independent variable
68 | Childs,F.,Aukett,A.,Darbyshire,P.,Ilett,S.,Livera,L. N.. Dietary education and iron deficiency anaemia in the inner city. Arch Dis Child. 1997;76:144-7. | Independent variable, Dependent variable
69 | Chirmulay,D.,Nisal,R.. Nutritional status of tribal underfive children in Ahmadnagar District, Maharashtra in relation to weaning/feeding practices. Indian Pediatr. 1993;30:215-22. | Study design, Age, Country
70 | Chmielewska,A.,Chmielewski,G.,Domellof,M.,Lewandowski,Z.,Szajewska,H.. Effect of iron supplementation on psychomotor development of non-anaemic, exclusively or predominantly breastfed infants: a randomised, controlled trial. BMJ Open. 2015;5:e009441. | Study design, Independent variable
71 | Chorell,E.,Karlsson Videhult,F.,Hernell,O.,Antti,H.,West,C. E.. Impact of probiotic feeding during weaning on the serum lipid profile and plasma metabolome in infants. Br J Nutr. 2013;110:116-26. | Independent variable, Dependent variable
72 | Christofides,A.,Schauer,C.,Zlotkin,S. H.. Iron deficiency and anemia prevalence and associated etiologic risk factors in First Nations and Inuit communities in Northern Ontario and Nunavut. Can J Public Health. 2005;96:304-7. | Study design
73 | Cook,J. D.,Reddy,M. B.,Burri,J.,Juillerat,M. A.,Hurrell,R. F.. The influence of different cereal grains on iron absorption from infant cereal foods. Am J Clin Nutr. 1997;65:964-9. | Independent variable, Dependent variable
74 | Cortese,M.,Riise,T.,Bjørnevik,K.,Holmøy,T.,Kampman,M. T.,Magalhaes,S.,Pugliatti,M.,Wolfson,C.,Myhr,K. M.. Timing of use of cod liver oil, a vitamin D source, and multiple sclerosis risk: The EnvIMS study. Multiple Sclerosis. 2015;21:1856-1864. | Age, Independent variable, Dependent variable
75 | Cosenza,L.,Pezzella,V.,Nocerino,R.,Di Costanzo,M.,Coruzzo,A.,Passariello,A.,Leone,L.,Savoia,M.,Del Puente,A.,Esposito,A.,Terrin,G.,Berni Canani,R.. Calcium and vitamin D intakes in children: a randomized controlled trial. BMC Pediatr. 2013;13:86. | Age, Independent variable
76 | Costa,A.,Oliveira,P.. About iron deficiency in early childhood. Nascer e Crescer. 2003;12:74-79. | Language
77 | Dagnelie,P. C.,van Staveren,W. A.,Vergote,F. J.,Dingjan,P. G.,van den Berg,H.,Hautvast,J. G.. Increased risk of vitamin B-12 and iron deficiency in infants on macrobiotic diets. Am J Clin Nutr. 1989;50:818-24. | Study design
78 | Dagnelie,P. C.,van Staveren,W. A.,Verschuren,S. A.,Hautvast,J. G.. Nutritional status of infants aged 4 to 18 months on macrobiotic diets and matched omnivorous control infants: a population-based mixed-longitudinal study. I. Weaning pattern, energy and nutrient intake. Eur J Clin Nutr. 1989;43:311-23. | Study design
79 | Dallman,P. R.. Inhibition of iron absorption by certain foods. Am J Dis Child. 1980;134:453-4. | Study design, Dependent variable
80 | Dalton,M. A.,Sargent,J. D.,O’Connor,G. T.,Olmstead,E. M.,Klein,R. Z.. Calcium and phosphorus supplementation of iron-fortified infant formula: no effect on iron status of healthy full-term infants. Am J Clin Nutr. 1997;65:921-6. | Independent variable
81 | Davidsson,L.,Jamil,K. A.,Sarker,S. A.,Zeder,C.,Fuchs,G.,Hurrell,R.. Human milk as a source of ascorbic acid: no enhancing effect on iron bioavailability from a traditional complementary food consumed by Bangladeshi infants and young children. Am J Clin Nutr. 2004;79:1073-7. | Country, Independent variable
82 | Davidsson,L.,Mackenzie,J.,Kastenmayer,P.,Aggett,P. J.,Hurrell,R. F.. Zinc and calcium apparent absorption from an infant cereal: a stable isotope study in healthy infants. Br J Nutr. 1996;75:291-300. | Independent variable, Dependent variable
83 | Davidsson,L.,Sarker,S. A.,Jamil,K. A.,Sultana,S.,Hurrell,R.. Regular consumption of a complementary food fortified with ascorbic acid and ferrous fumarate or ferric pyrophosphate is as useful as ferrous sulfate in maintaining hemoglobin concentrations >105 g/L in young Bangladeshi children. Am J Clin Nutr. 2009;89:1815-20. | Independent variable
84 | Davis,J. R.,Jr.,Goldenring,J.,Lubin,B. H.. Nutritional vitamin B12 deficiency in infants. Am J Dis Child. 1981;135:566-7. | Study design
85 | Dawodu,A.,Davidson,B.,Woo,J. G.,Peng,Y. M.,Ruiz-Palacios,G. M.,de Lourdes Guerrero,M.,Morrow,A. L.. Sun exposure and vitamin D supplementation in relation to vitamin D status of breastfeeding mothers and infants in the global exploration of human milk study. Nutrients. 2015;7:1081-93. | Independent variable
86 | de Almeida,C. A.,Dutra-De-Oliveira,J. E.,Crott,G. C.,Cantolini,A.,Ricco,R. G.,Del Ciampo,L. A.,Baptista,M. E.. Effect of fortification of drinking water with iron plus ascorbic acid or with ascorbic acid alone on hemoglobin values and anthropometric indicators in preschool children in day-care centers in Southeast Brazil. Food Nutr Bull. 2005;26:259-65. | Age, Independent variable
87 | de Freitas,C. L.,Romani,S.,Amigo,H.. Breast-feeding and malnutrition in rural areas of northeast Brazil. Bull Pan Am Health Organ. 1986;20:138-46. | Study design, Independent variable, Dependent variable
88 | Deegan,K. L.,Jones,K. M.,Zuleta,C.,Ramirez-Zea,M.,Lildballe,D. L.,Nexo,E.,Allen,L. H.. Breast milk vitamin B-12 concentrations in Guatemalan women are correlated with maternal but not infant vitamin B-12 status at 12 months postpartum. J Nutr. 2012;142:112-6. | Independent variable
89 | Delgado,H. L.,Martorell,R.,Klein,R. E.. Nutrition, lactation, and birth interval components in rural Guatemala. Am J Clin Nutr. 1982;35:1468-76. | Country, Dependent variable
90 | Dewey,K. G.,Cohen,R. J.,Brown,K. H.,Rivera,L. L.. Effects of exclusive breastfeeding for four versus six months on maternal nutritional status and infant motor development: results of two randomized trials in Honduras. J Nutr. 2001;131:262-7. | Dependent variable
91 | Dewey,K. G.,Cohen,R. J.,Rivera,L. L.,Brown,K. H.. Effects of age of introduction of complementary foods on iron status of breast-fed infants in Honduras. Am J Clin Nutr. 1998;67:878-84. | Country
92 | Dewey,K. G.,Domellof,M.,Cohen,R. J.,Landa Rivera,L.,Hernell,O.,Lonnerdal,B.. Iron supplementation affects growth and morbidity of breast-fed infants: results of a randomized trial in Sweden and Honduras. J Nutr. 2002;132:3249-55. | Independent variable
93 | Dewey,K. G.,Huffman,S. L.. Maternal, infant, and young child nutrition: combining efforts to maximize impacts on child growth and micronutrient status. Food Nutr Bull. 2009;30:S187-9. | Study design
94 | Dewey,K. G.,Lonnerdal,B.. Milk and nutrient intake of breast-fed infants from 1 to 6 months: relation to growth and fatness. J Pediatr Gastroenterol Nutr. 1983;2:497-506. | Dependent variable
95 | Dewey,K. G.,Reinhart,G. A.. Introduction. Fatty acid status in early life in low-income countries: determinants & consequences. Matern Child Nutr. 2011;7 Suppl 2:1. | Study design
96 | Dewey,K. G.,Romero-Abal,M. E.,Quan de Serrano,J.,Bulux,J.,Peerson,J. M.,Eagle,P.,Solomons,N. W.. Effects of discontinuing coffee intake on iron status of iron-deficient Guatemalan toddlers: a randomized intervention study. Am J Clin Nutr. 1997;66:168-76. | Country
97 | Dewey,K.. Meeting protein needs at 6 to 24 months of age. Food Nutr Bull. 2013;34:240-1. | Study design
98 | Diana,L. Culbertson Jamie L. Westcott Laurie Sherlock K. Michael Hambidge Nancy F. Krebs. Zinc (Zn) Intake from Different Complementary Feeding (CF) Regimens. Pediatric Academic Societies Annual Meeting. 2011. | Study design
99 | Dickson,N.,Morison,I.. Iron deficiency in infants of Cambodian refugees. N Z Med J. 1992;105:83-4. | Study design, Country
100 | Dine,M. S.. Evaluation of the free erythrocyte porphyrin (FEP) test in a private practice: the incidence of iron deficiency and increased lead absorption in 9- to 13-month-old infants. Pediatrics. 1980;65:303-6. | Study design
101 | Domellof,M.,Cohen,R. J.,Dewey,K. G.,Hernell,O.,Rivera,L. L.,Lonnerdal,B.. Iron supplementation of breast-fed Honduran and Swedish infants from 4 to 9 months of age. J Pediatr. 2001;138:679-87. | Independent variable
102 | Domellof,M.,Lonnerdal,B.,Abrams,S. A.,Hernell,O.. Iron absorption in breast-fed infants: effects of age, iron status, iron supplements, and complementary foods. Am J Clin Nutr. 2002;76:198-204. | Independent variable, Dependent variable
103 | Domellof,M.,Lonnerdal,B.,Dewey,K. G.,Cohen,R. J.,Rivera,L. L.,Hernell,O.. Sex differences in iron status during infancy. Pediatrics. 2002;110:545-52. | Independent variable
104 | Dong,C.,Ge,P.,Ren,X.,Wang,J.,Fan,H.,Yan,X.,Yin,S. A.. Prospective study on the effectiveness of complementary food supplements on improving status of elder infants and young children in the areas affected by Wenchuan earthquake. PLoS One. 2013;8:e72711. | Study design, Health Status
105 | Dong,C.,Ge,P.,Ren,X.,Zhao,X.,Wang,J.,Fan,H.,Yin,S. A.. Growth and anaemia among infants and young children for two years after the Wenchuan earthquake. Asia Pac J Clin Nutr. 2014;23:445-51. | Study design, Health Status
106 | Dorea,J. G.,Furumoto,R. A.. Infant feeding practices among poor families of an urban squatter community. Ann Nutr Metab. 1992;36:257-64. | Study design, Dependent variable
107 | Doron,D.,Hershkop,K.,Granot,E.. Nutritional deficits resulting from an almond-based infant diet. Clin Nutr. 2001;20:259-61. | Study design
108 | Du Plessis,L. M.,Kruger,H. S.,Sweet,L.. Complementary feeding: a critical window of opportunity from six months onwards. South African Journal of Clinical Nutrition. 2013;26:S129-40 1p. | Study design
109 | Dube,K.,Schwartz,J.,Mueller,M. J.,Kalhoff,H.,Kersting,M.. Iron intake and iron status in breastfed infants during the first year of life. Clin Nutr. 2010;29:773-8. | Independent variable
110 | Duggan,C.,Penny,M. E.,Hibberd,P.,Gil,A.,Huapaya,A.,Cooper,A.,Coletta,F.,Emenhiser,C.,Kleinman,R. E.. Oligofructose-supplemented infant cereal: 2 randomized, blinded, community-based trials in Peruvian infants. Am J Clin Nutr. 2003;77:937-42. | Independent variable
111 | Dunne,A.. Nutrition in infancy: achieving nutrition needs for new mothers and children. Br J Community Nurs. 2012;Suppl:S22. | Study design
112 | Durnin,J. V.,Aitchison,T. C.,Beckett,C.,Husaini,M.,Pollitt,E.. Nutritional intake of an undernourished infant population receiving an energy and micronutrient supplement in Indonesia. Eur J Clin Nutr. 2000;54 Suppl 2:S43-51. | Country, Health Status, Independent variable
113 | Dutra-de-Oliveira,J. E.,Lamounier,J. A.,de Almeida,C. A.,Marchini,J. S.. Fortification of drinking water to control iron-deficiency anemia in preschool children. Food Nutr Bull. 2007;28:173-80. | Age, Independent variable
114 | D’Vaz,N.,Meldrum,S. J.,Dunstan,J. A.,Martino,D.,McCarthy,S.,Metcalfe,J.,Tulic,M. K.,Mori,T. A.,Prescott,S. L.. Postnatal fish oil supplementation in high-risk infants to prevent allergy: randomized controlled trial. Pediatrics. 2012;130:674-82. | Independent variable
115 | Ekbote,V. H.,Khadilkar,A. V.,Chiplonkar,S. A.,Hanumante,N. M.,Khadilkar,V. V.,Mughal,M. Z.. A pilot randomized controlled trial of oral calcium and vitamin D supplementation using fortified laddoos in underprivileged Indian toddlers. Eur J Clin Nutr. 2011;65:440-6. | Age
116 | Elalfy,M. S.,Hamdy,A. M.,Maksoud,S. S.,Megeed,R. I.. Pattern of milk feeding and family size as risk factors for iron deficiency anemia among poor Egyptian infants 6 to 24 months old. Nutr Res. 2012;32:93-9. | Study design, Country
117 | Emmett,P. M.,Jones,L. R.. Diet and growth in infancy: relationship to socioeconomic background and to health and development in the Avon Longitudinal Study of Parents and Children. Nutr Rev. 2014;72:483-506. | Study design, Independent variable, Dependent variable
118 | Eneroth,H.,El Arifeen,S.,Persson,L. A.,Kabir,I.,Lonnerdal,B.,Hossain,M. B.,Ekstrom,E. C.. Duration of exclusive breast-feeding and infant iron and zinc status in rural Bangladesh. J Nutr. 2009;139:1562-7. | Country, Independent variable
119 | Eneroth,H.,El Arifeen,S.,Persson,L. A.,Lonnerdal,B.,Hossain,M. B.,Stephensen,C. B.,Ekstrom,E. C.. Maternal multiple micronutrient supplementation has limited impact on micronutrient status of Bangladeshi infants compared with standard iron and folic acid supplementation. J Nutr. 2010;140:618-24. | Country, Independent variable
120 | Eneroth,H.,Persson,L. A.,El Arifeen,S.,Ekstrom,E. C.. Infant anaemia is associated with infection, low birthweight and iron deficiency in rural Bangladesh. Acta Paediatr. 2011;100:220-5. | Country, Independent variable
121 | Engelmann,M. D.,Davidsson,L.,Sandstrom,B.,Walczyk,T.,Hurrell,R. F.,Michaelsen,K. F.. The influence of meat on nonheme iron absorption in infants. Pediatr Res.. 1998;43:768-73. | Independent variable, Dependent variable
122 | Faber,M.,Benade,A. J.. Perceptions of infant cereals and dietary intakes of children aged 4-24 months in a rural South African community. Int J Food Sci Nutr. 2001;52:359-65. | Study design, Country, Dependent variable
123 | Faber,M.,Kvalsvig,J. D.,Lombard,C. J.,Benade,A. J.. Effect of a fortified maize-meal porridge on anemia, micronutrient status, and motor development of infants. Am J Clin Nutr. 2005;82:1032-9. | Country, Health Status, Independent variable
124 | Faber,M.. Dietary intake and anthropometric status differ for anaemic and non-anaemic rural South African infants aged 6-12 months. J Health Popul Nutr. 2007;25:285-93. | Study design, Country
125 | Fahmida,U.,Kolopaking,R.,Santika,O.,Sriani,S.,Umar,J.,Htet,M. K.,Ferguson,E.. Effectiveness in improving knowledge, practices, and intakes of “key problem nutrients” of a complementary feeding intervention developed by using linear programming: experience in Lombok, Indonesia. Am J Clin Nutr. 2015;101:455-61. | Dependent variable
126 | Fairweather-Tait,S. J.,Wharf,S. G.,Fox,T. E.. Zinc absorption in infants fed iron-fortified weaning food. Am J Clin Nutr. 1995;62:785-9. | Independent variable, Dependent variable
127 | Fairweather-Tait,S.,Fox,T.,Wharf,S. G.,Eagles,J.. The bioavailability of iron in different weaning foods and the enhancing effect of a fruit drink containing ascorbic acid. Pediatr Res. 1995;37:389-94. | Independent variable, Dependent variable
128 | Fawzi,W. W.,Forman,M. R.,Levy,A.,Graubard,B. I.,Naggan,L.,Berendes,H. W.. Maternal anthropometry and infant feeding practices in Israel in relation to growth in infancy: the North African Infant Feeding Study. Am J Clin Nutr. 1997;65:1731-7. | Dependent variable
129 | Fawzi,W. W.,Herrera,M. G.,Nestel,P.,el Amin,A.,Mohamed,K. A.. A longitudinal study of prolonged breastfeeding in relation to child undernutrition. Int J Epidemiol. 1998;27:255-60. | Country, Dependent variable
130 | Ferrara,M.,Bertocco,F.,Ricciardi,A.,Ferrara,D.,Incarnato,L.,Capozzi,L.. Iron deficiency screening in the first three years of life: a three-decade-long retrospective case study. Hematology. 2014;19:239-43. | Study design
131 | Ferraz,I. S.,Daneluzzi,J. C.,Vannucchi,H.. Vitamin A deficiency in children aged 6 to 24 months in Sao Paulo State, Brazil. Nutrition Research. 2000;20:757-768. | Independent variable, Dependent variable
132 | Ferris,A. G.,Laus,M. J.,Hosmer,D. W.,Beal,V. A.. The effect of diet on weight gain in infancy. Am J Clin Nutr. 1980;33:2635-42. | Dependent variable
133 | Fewtrell,M.. 2.4 Complementary foods. World Rev Nutr Diet. 2015;113:109-12. | Study design
134 | Fildes,V.. Weaning: on the bottle again. Nurs Mirror. 1980;151:18-21. | Study design
135 | Fomon,S. J.,Ziegler,E. E.,Nelson,S. E.,Edwards,B. B.. Cow milk feeding in infancy: gastrointestinal blood loss and iron nutritional status. J Pediatr. 1981;98:540-5. | Independent variable
136 | Fomon,S. J.. Bioavailability of supplemental iron in commercially prepared dry infant cereals. J Pediatr. 1987;110:660-1. | Study design, Dependent variable
137 | Fomon,S. J.. Feeding normal infants: rationale for recommendations. J Am Diet Assoc. 2001;101:1002-5. | Study design
138 | Forsyth,S.. Meeting nutrient needs in the first 1,000 days of life. Ann Nutr Metab. 2014;65:2-3. | Study design
139 | Friel,J. K.,Andrews,W. L.,Simmons,B. S.,L’Abbe,M. R.,Mercer,C.,MacDonald,A.,McCloy,U. R.. Evaluation of full-term infants fed an evaporated milk formula. Acta Paediatr. 1997;86:448-53. | Independent variable
140 | Frontela,C.,Scarino,M. L.,Ferruzza,S.,Ros,G.,Martinez,C.. Effect of dephytinization on bioavailability of iron, calcium and zinc from infant cereals assessed in the Caco-2 cell model. World J Gastroenterol. 2009;15:1977-84. | Study design, Health Status
141 | Gallo,S.,Comeau,K.,Vanstone,C.,Agellon,S.,Sharma,A.,Jones,G.,L’Abbe,M.,Khamessan,A.,Rodd,C.,Weiler,H.. Effect of different dosages of oral vitamin D supplementation on vitamin D status in healthy, breastfed infants: a randomized trial. Jama. 2013;309:1785-92. | Independent variable
142 | Gan,C. Y.,Chin,B.,Teoh,S. T.,Chan,M. K.. Nutritional status of Kadazan children in a rural district in Sabah, Malaysia. Southeast Asian J Trop Med Public Health. 1993;24:293-301. | Study design, Age
143 | Garry,P. J.,Owen,G. M.,Hooper,E. M.,Gilbert,B. A.. Iron absorption from human milk and formula with and without iron supplementation. Pediatr Res. 1981;15:822-8. | Independent variable
144 | Gibson,R. S.,Hotz,C.. The adequacy of micronutrients in complementary foods. Pediatrics. 2000;106:1298-9. | Study design
145 | Gibson,S.,Sidnell,A.. Nutrient adequacy and imbalance among young children aged 1-3 years in the UK. Nutrition Bulletin. 2013;39:172-180 9p. | Study design
146 | Glinz,D.,Hurrell,R. F.,Ouattara,M.,Zimmermann,M. B.,Brittenham,G. M.,Adiossan,L. G.,Righetti,A. A.,Seifert,B.,Diakité,V. G.,Utzinger,J.,N’Goran,E. K.,Wegmüller,R.. The effect of iron-fortified complementary food and intermittent preventive treatment of malaria on anaemia in 12- to 36-month-old children: A cluster-randomised controlled trial. Malaria Journal. 2015;14. | Country, Independent variable
147 | Godel,J. C.,Pabst,H. F.,Hodges,P. E.,Johnson,K. E.. Iron status and pregnancy in a northern Canadian population: relationship to diet and iron supplementation. Can J Public Health. 1992;83:339-43. | Independent variable
148 | Gokcay,G.,Ozden,T.,Karakas,Z.,Karabayir,N.,Yildiz,I.,Abali,S.,Sahip,Y.. Effect of iron supplementation on development of iron deficiency anemia in breastfed infants. J Trop Pediatr. 2012;58:481-5. | Independent variable
149 | Gondolf,U. H.,Tetens,I.,Michaelsen,K. F.,Trolle,E.. Iron supplementation is positively associated with increased serum ferritin levels in 9-month-old Danish infants. Br J Nutr. 2013;109:103-10. | Study design
150 | Gopaldas,T.,John,C.. Evaluation of a controlled 6 months feeding trial on intake by infants and toddlers fed a high energy-low bulk gruel versus a high energy-high bulk gruel in addition to their habitual home diet. J Trop Pediatr. 1992;38:278-83. | Dependent variable
151 | Gorczyca,D.,Prescha,A.,Szeremeta,K.,Jankowski,A.. Iron status and dietary iron intake of vegetarian children from Poland. Ann Nutr Metab. 2013;62:291-7. | Study design
152 | Graham,E. A.,Carlson,T. H.,Sodergren,K. K.,Detter,J. C.,Labbe,R. F.. Delayed bottle weaning and iron deficiency in southeast Asian toddlers. West J Med. 1997;167:10-4. | Study design, Independent variable
153 | Grant,C. C.,Wall,C. R.,Brunt,D.,Crengle,S.,Scragg,R.. Population prevalence and risk factors for iron deficiency in Auckland, New Zealand. J Paediatr Child Health. 2007;43:532-8. | Study design
154 | Greer,F. R.,Marshall,S.. Bone mineral content, serum vitamin D metabolite concentrations, and ultraviolet B light exposure in infants fed human milk with and without vitamin D2 supplements. J Pediatr. 1989;114:204-12. | Independent variable
155 | Greer,F. R.,Searcy,J. E.,Levin,R. S.,Steichen,J. J.,Steichen-Asche,P. S.,Tsang,R. C.. Bone mineral content and serum 25-hydroxyvitamin D concentrations in breast-fed infants with and without supplemental vitamin D: one-year follow-up. J Pediatr. 1982;100:919-22. | Independent variable
156 | Guerin-Danan,C.,Chabanet,C.,Pedone,C.,Popot,F.,Vaissade,P.,Bouley,C.,Szylit,O.,Andrieux,C.. Milk fermented with yogurt cultures and Lactobacillus casei compared with yogurt and gelled milk: influence on intestinal microflora in healthy infants. Am J Clin Nutr. 1998;67:111-7. | Independent variable
157 | Guldan,G. S.,Fan,H. C.,Ma,X.,Ni,Z. Z.,Xiang,X.,Tang,M. Z.. Culturally appropriate nutrition education improves infant feeding and growth in rural Sichuan, China. J Nutr. 2000;130:1204-11. | Independent variable
158 | Gupta,S.,Venkateswaran,R.,Gorenflo,D. W.,Eyler,A. E.. Childhood iron deficiency anemia, maternal nutritional knowledge, and maternal feeding practices in a high-risk population. Prev Med. 1999;29:152-6. | Study design
159 | Haider,R.,Islam,A.,Kabir,I.,Habte,D.. Early complementary feeding is associated with low nutritional status of young infants recovering from diarrhoea. J Trop Pediatr. 1996;42:170-2. | Health Status
160 | Han,Y. H.,Yon,M.,Han,H. S.,Johnston,K. E.,Tamura,T.,Hyun,T.. Zinc status and growth of Korean infants fed human milk, casein-based, or soy-based formula: three-year longitudinal study. Nutr Res Pract. 2011;5:46-51. | Independent variable
161 | Han,Y. H.,Yon,M.,Han,H. S.,Kim,K. Y.,Tamura,T.,Hyun,T. H.. Folate contents in human milk and casein-based and soya-based formulas, and folate status in Korean infants. Br J Nutr. 2009;101:1769-74. | Independent variable
162 | Hanna,M. D.,Vogelgesang,S. A.,Carroll,N. L.,Murphy,K. K.. Dietary megaloblastic anemia in an infant. S D J Med. 1986;39:7-9. | Study design
163 | Harahap,H.,Jahari,A. B.,Husaini,M. A.,Saco-Pollitt,C.,Pollitt,E.. Effects of an energy and micronutrient supplement on iron deficiency anemia, physical activity and motor and mental development in undernourished children in Indonesia. Eur J Clin Nutr. 2000;54 Suppl 2:S114-9. | Country, Independent variable
164 | Harbild,H. L.,Harslof,L. B.,Christensen,J. H.,Kannass,K. N.,Lauritzen,L.. Fish oil-supplementation from 9 to 12 months of age affects infant attention in a free-play test and is related to change in blood pressure. Prostaglandins Leukot Essent Fatty Acids. 2013;89:327-33. | Independent variable
165 | Harrington,M.,Hotz,C.,Zeder,C.,Polvo,G. O.,Villalpando,S.,Zimmermann,M. B.,Walczyk,T.,Rivera,J. A.,Hurrell,R. F.. A comparison of the bioavailability of ferrous fumarate and ferrous sulfate in non-anemic Mexican women and children consuming a sweetened maize and milk drink. Eur J Clin Nutr. 2011;65:20-5. | Study design, Independent variable
166 | Hasan,J.,Ray,J.,Khan,Z.. Role of weaning in the nutritional status of infant--a longitudinal study in the rural area of Aligarh. J Indian Med Assoc. 1996;94:169, 215. | Study design, Country, Dependent variable
167 | Hay,G.,Clausen,T.,Whitelaw,A.,Trygg,K.,Johnston,C.,Henriksen,T.,Refsum,H.. Maternal folate and cobalamin status predicts vitamin status in newborns and 6-month-old infants. J Nutr. 2010;140:557-64. | Independent variable
168 | Hemalatha,P.,Bhaskaram,P.,Kumar,P. A.,Khan,M. M.,Islam,M. A.. Zinc status of breastfed and formula-fed infants of different gestational ages. J Trop Pediatr. 1997;43:52-4. | Study design, Independent variable
169 | Herman,S.,Griffin,I. J.,Suwarti,S.,Ernawati,F.,Permaesih,D.,Pambudi,D.,Abrams,S. A.. Cofortification of iron-fortified flour with zinc sulfate, but not zinc oxide, decreases iron absorption in Indonesian children. Am J Clin Nutr. 2002;76:813-7. | Country, Independent variable
170 | Ho,M. L.,Yen,H. C.,Tsang,R. C.,Specker,B. L.,Chen,X. C.,Nichols,B. L.. Randomized study of sunshine exposure and serum 25-OHD in breast-fed infants in Beijing, China. J Pediatr. 1985;107:928-31. | Independent variable
171 | Hoffman,D. R.,Birch,E. E.,Birch,D. G.,Uauy,R.,Castaneda,Y. S.,Lapus,M. G.,Wheaton,D. H.. Impact of early dietary intake and blood lipid composition of long-chain polyunsaturated fatty acids on later visual development. J Pediatr Gastroenterol Nutr. 2000;31:540-53. | Independent variable
172 | Hokama,T.. Levels of serum ferritin and total body iron among infants with different feeding regimens. Acta Paediatr Jpn. 1993;35:298-301. | Independent variable
173 | Holmes,S.. Infant feeding. The young vegetarian. Nurs Times. 1987;83:51-5. | Study design
174 | Hop le,T.,Berger,J.. Multiple micronutrient supplementation improves anemia, micronutrient nutrient status, and growth of Vietnamese infants: double-blind, randomized, placebo-controlled trial. J Nutr. 2005;135:660s-665s. | Country, Independent variable
175 | Hopkins,D.,Emmett,P.,Steer,C.,Rogers,I.,Noble,S.,Emond,A.. Infant feeding in the second 6 months of life related to iron status: an observational study. Arch Dis Child. 2007;92:850-4. | Independent variable
176 | Hoyos,C.,Almqvist,C.,Garden,F.,Xuan,W.,Oddy,W. H.,Marks,G. B.,Webb,K. L.. Effect of omega 3 and omega 6 fatty acid intakes from diet and supplements on plasma fatty acid levels in the first 3 years of life. Asia Pac J Clin Nutr. 2008;17:552-7. | Independent variable
177 | Huang,S. C.,Yang,Y. J.,Cheng,C. N.,Chen,J. S.,Lin,C. H.. The etiology and treatment outcome of iron deficiency and iron deficiency anemia in children. J Pediatr Hematol Oncol. 2010;32:282-5. | Study design
178 | Hurrell,R. F.,Reddy,M. B.,Juillerat,M. A.,Cook,J. D.. Degradation of phytic acid in cereal porridges improves iron absorption by human subjects. Am J Clin Nutr. 2003;77:1213-9. | Study design, Age
179 | Hurrell,R. F.. Iron fortification of infant cereals. Bibl Nutr Dieta. 1989:114-22. | Study design
180 | Husaini,M. A.,Jahari,A. B.,Pollitt,E.. The effects of high energy and micronutrient supplementation on iron status in nutritionally at risk infants. Biomed Environ Sci. 1996;9:325-40. | Country, Health Status, Independent variable
181 | Huybregts,L.,Houngbe,F.,Salpeteur,C.,Brown,R.,Roberfroid,D.,Ait-Aissa,M.,Kolsteren,P.. The effect of adding ready-to-use supplementary food to a general food distribution on child nutritional status and morbidity: a cluster-randomized controlled trial. PLoS Med. 2012;9:e1001313. | Country, Independent variable
182 | Innis,S. M.,Nelson,C. M.,Wadsworth,L. D.,MacLaren,I. A.,Lwanga,D.. Incidence of iron-deficiency anaemia and depleted iron stores among nine-month-old infants in Vancouver, Canada. Can J Public Health. 1997;88:80-4. | Study design
183 | Iqbal Hossain,M.,Yasmin,R.,Kabir,I.. Nutritional and immunisation status, weaning practices and socio-economic conditions of under five children in three villages of Bangladesh. Indian J Public Health. 1999;43:37-41. | Study design, Country, Health Status
184 | Isherwood,R. J.,Dimond,C.,Longhurst,S.. Breast feeding and weaning practices in relation to nutritional status of under-5 children in north Bangladesh. J Trop Pediatr. 1988;34:28-31. | Study design, Country
185 | Islam,M. A.,Ahmed,T.,Faruque,A. S.,Rahman,S.,Das,S. K.,Ahmed,D.,Fattori,V.,Clarke,R.,Endtz,H. P.,Cravioto,A.. Microbiological quality of complementary foods and its association with diarrhoeal morbidity and nutritional status of Bangladeshi children. Eur J Clin Nutr. 2012;66:1242-6. | Study design, Dependent variable
186 | Jaber,L.. Preventive intervention for iron deficiency anaemia in a high risk population. Int J Risk Saf Med. 2014;26:155-62. | Independent variable
187 | Jain,V.,Klein,B. P.,Nash,M.,Chapman-Novakofski,K.. Two feasibility studies for introduction of multimicronutrient soy/whey-based supplements in rural homes in Honduras. Journal of Hunger and Environmental Nutrition. 2011;6:247-263. | Country, Independent variable
188 | Jalla,S.,Westcott,J.,Steirn,M.,Miller,L. V.,Bell,M.,Krebs,N. F.. Zinc absorption and exchangeable zinc pool sizes in breast-fed infants fed meat or cereal as first complementary food. J Pediatr Gastroenterol Nutr. 2002;34:35-41. | Dependent variable
189 | James,J.,Evans,J.,Male,P.,Pallister,C.,Hendrikz,J. K.,Oakhill,A.. Iron deficiency in inner city pre-school children: development of a general practice screening programme. J R Coll Gen Pract. 1988;38:250-2. | Study design, Age
190 | Jansen,G.R.,O’B Hourihane. The nutritional status of preschool children in Egypt. World Rev Nutr Diet. 1985;45:42-67. | Study design, Age
191 | Jatanasen,A.,Sacholvicharn,V.,Ongkulna,P.. An evaluation of supplementary feedings of Thai infants in urban slum communities: effect on growth, health and nutritional status. J Med Assoc Thai. 1983;66 Suppl 1:20-9. | Health Status, Dependent variable
192 | Johnson,E. J.,Goyea,H. S.,Ogbeide,M. I.. Nutritional status and weaning patterns of Benin City children. East Afr Med J. 1980;57:405-11. | Country
193 | Jones,K. M.,Ramirez-Zea,M.,Zuleta,C.,Allen,L. H.. Prevalent vitamin B-12 deficiency in twelve-month-old Guatemalan infants is predicted by maternal B-12 deficiency and infant diet. J Nutr. 2007;137:1307-13. | Study design, Independent variable
194 | Kallio,M. J.,Salmenpera,L.,Siimes,M. A.,Perheentupa,J.,Miettinen,T. A.. Exclusive breast-feeding and weaning: effect on serum cholesterol and lipoprotein concentrations in infants during the first year of life. Pediatrics. 1992;89:663-6. | Independent variable, Dependent variable
195 | Karlsson Videhult,F.,Ohlund,I.,Stenlund,H.,Hernell,O.,West,C. E.. Probiotics during weaning: a follow-up study on effects on body composition and metabolic markers at school age. Eur J Nutr. 2015;54:355-63. | Age, Independent variable
196 | Khokhar,A.,Singh,S.,Talwar,R.,Rasania,S. K.,Badhan,S. R.,Mehra,M.. A study of malnutrition among children aged 6 months to 2 years from a resettlement colony of Delhi. Indian J Med Sci. 2003;57:286-9. | Study design, Country, Health Status
197 | Kim,M. J.,Na,B.,No,S. J.,Han,H. S.,Jeong,E. H.,Lee,W.,Han,Y.,Hyeun,T.. Nutritional status of vitamin D and the effect of vitamin D supplementation in Korean breast-fed infants. J Korean Med Sci. 2010;25:83-9. | Independent variable
198 | Kohn,G.,Sawatzki,G.,van Biervliet,J. P.. Long-chain polyunsaturated fatty acids in infant nutrition. Eur J Clin Nutr. 1994;48 Suppl 2:S1-7. | Independent variable
199 | Krebs,N. F. Culbertson D. L. Westcott J. L. Sherlock L. Hambidge K. M.. Normal Iron Status in Breastfed Infants Consuming Meat as an Early Complementary Food. Pediatric Academic Societies Annual Meeting. 2011. | Study design
200 | Krebs,N. F.,Hambidge,K. M.,Mazariegos,M.,Westcott,J.,Goco,N.,Wright,L. L.,Koso-Thomas,M.,Tshefu,A.,Bose,C.,Pasha,O.,Goldenberg,R.,Chomba,E.,Carlo,W.,Kindem,M.,Das,A.,Hartwell,T.,McClure,E.. Complementary feeding: a Global Network cluster randomized controlled trial. BMC Pediatr. 2011;11:4. | Study design, Country
201 | Krebs,N. F.,Hambidge,K. M.,Westcott,J. E.,Miller,L. V.,Sian,L.,Bell,M.,Grunwald,G.. Exchangeable zinc pool size in infants is related to key variables of zinc homeostasis. J Nutr. 2003;133:1498s-501s. | Dependent variable
202 | Krebs,N. F.,Mazariegos,M.,Chomba,E.,Sami,N.,Pasha,O.,Tshefu,A.,Carlo,W. A.,Goldenberg,R. L.,Bose,C. L.,Wright,L. L.,Koso-Thomas,M.,Goco,N.,Kindem,M.,McClure,E. M.,Westcott,J.,Garces,A.,Lokangaka,A.,Manasyan,A.,Imenda,E.,Hartwell,T. D.,Hambidge,K. M.. Randomized controlled trial of meat compared with multimicronutrient-fortified cereal in infants and toddlers with high stunting rates in diverse settings. Am J Clin Nutr. 2012;96:840-7. | Country
203 | Krebs,N. F.,Reidinger,C. J.,Robertson,A. D.,Hambidge,K. M.. Growth and intakes of energy and zinc in infants fed human milk. J Pediatr. 1994;124:32-9. | Dependent variable
204 | Kreiter,S. R.,Schwartz,R. P.,Kirkman,H. N.,Jr.,Charlton,P. A.,Calikoglu,A. S.,Davenport,M. L.. Nutritional rickets in African American breast-fed infants. J Pediatr. 2000;137:153-7. | Study design, Health Status
205 | Kuipers,R. S.,Luxwolda,M. F.,Sango,W. S.,Kwesigabo,G.,Dijck-Brouwer,D. A.,Muskiet,F. A.. Postdelivery changes in maternal and infant erythrocyte fatty acids in 3 populations differing in fresh water fish intakes. Prostaglandins Leukot Essent Fatty Acids. 2011;85:387-97. | Independent variable
206 | Ladhani,S.,Srinivasan,L.,Buchanan,C.,Allgrove,J.. Presentation of vitamin D deficiency. Arch Dis Child. 2004;89:781-4. | Study design, Health Status, Independent variable
207 | Lampe,J. B.,Velez,N.. The effect of prolonged bottle feeding on cow’s milk intake and iron stores at 18 months of age. Clin Pediatr (Phila). 1997;36:569-72. | Independent variable, Dependent variable
208 | Lande,B.,Andersen,L. F.,Baerug,A.,Trygg,K. U.,Lund-Larsen,K.,Veierod,M. B.,Bjorneboe,G. E.. Infant feeding practices and associated factors in the first six months of life: the Norwegian infant nutrition survey. Acta Paediatr. 2003;92:152-61. | Study design, Dependent variable
209 | Lartey,A.,Manu,A.,Brown,K. H.,Dewey,K. G.. Predictors of micronutrient status among six- to twelve-month-old breast-fed Ghanaian infants. J Nutr. 2000;130:199-207. | Country
210 | Lartey,A.,Manu,A.,Brown,K. H.,Peerson,J. M.,Dewey,K. G.. A randomized, community-based trial of the effects of improved, centrally processed complementary foods on growth and micronutrient status of Ghanaian infants from 6 to 12 mo of age. Am J Clin Nutr. 1999;70:391-404. | Country
211 | Lartey,A.,Manu,A.,Brown,K. H.,Peerson,J. M.,Dewey,K. G.. Predictors of growth from 1 to 18 months among breast-fed Ghanaian infants. Eur J Clin Nutr. 2000;54:41-9. | Country
212 | Lauritzen,L.,Hoppe,C.,Straarup,E. M.,Michaelsen,K. F.. Maternal fish oil supplementation in lactation and growth during the first 2.5 years of life. Pediatr Res. 2005;58:235-42. | Independent variable
213 | Lavon,B.,Tulchinsky,T. H.,Preger,M.,Said,R.,Kaufman,S.. Iron deficiency anemia among Jewish and Arab infants at 6 and 12 months of age in Hadera, Israel. Isr J Med Sci. 1985;21:107-12. | Study design, Independent variable
214 | Lehmann,F.,Gray-Donald,K.,Mongeon,M.,Di Tommaso,S.. Iron deficiency anemia in 1-year-old children of disadvantaged families in Montreal. Cmaj. 1992;146:1571-7. | Study design
215 | Lehtonen,E.,Ormisson,A.,Nucci,A.,Cuthbertson,D.,Sorkio,S.,Hyytinen,M.,Alahuhta,K.,Berseth,C.,Salonen,M.,Taback,S., Franciscus,M.,Gonzalez-Frutos,T.,Korhonen,T. E.,Lawson,M. L.,Becker,D. J.,Krischer,J. P.,Knip,M.,Virtanen,S. M.. Use of vitamin D supplements during infancy in an international feeding trial. Public Health Nutr. 2014;17:810-22. | Independent variable, Dependent variable
216 | Leung,S. S.,Davies,D. P.,Lui,S.,Lo,L.,Yuen,P.,Swaminathan,R.,Hom,B. L.. Iron status of Hong Kong babies at 18 months. J Singapore Paediatr Soc. 1987;29 Suppl 1:108-12. | Independent variable, Dependent variable
217 | Leung,S. S.,Lui,S.,Swaminathan,R.. Vitamin D status of Hong Kong Chinese infants. Acta Paediatr Scand. 1989;78:303-6. | Study design, Independent variable
218 | Lind,T.,Persson,L.,Lonnerdal,B.,Stenlund,H.,Hernell,O.. Effects of weaning cereals with different phytate content on growth, development and morbidity: a randomized intervention trial in infants from 6 to 12 months of age. Acta Paediatr. 2004;93:1575-82. | Dependent variable
219 | Lioret,S.,McNaughton,S. A.,Spence,A. C.,Crawford,D.,Campbell,K. J.. Tracking of dietary intakes in early childhood: the Melbourne InFANT Program. Eur J Clin Nutr. 2013;67:275-81. | Dependent variable
220 | Lönnerdal,B.,Hernell,O.. Under and over nutrition of iron in infancy and early childhood. Pakistan Paediatric Journal. 2014;38:132-133. | Study design
221 | Lopez de Romana,G.,Cusirramos,S.,Lopez de Romana,D.,Gross,R.. Efficacy of multiple micronutrient supplementation for improving anemia, micronutrient status, growth, and morbidity of Peruvian infants. J Nutr. 2005;135:646s-652s. | Independent variable
222 | Lozoff,B.,De Andraca,I.,Castillo,M.,Smith,J. B.,Walter,T.,Pino,P.. Behavioral and developmental effects of preventing iron-deficiency anemia in healthy full-term infants. Pediatrics. 2003;112:846-54. | Independent variable
223 | Lozoff,B.,Kaciroti,N.,Walter,T.. Iron deficiency in infancy: applying a physiologic framework for prediction. Am J Clin Nutr. 2006;84:1412-21. | Independent variable
224 | Lundeen,E.,Schueth,T.,Toktobaev,N.,Zlotkin,S.,Hyder,S. M.,Houser,R.. Daily use of Sprinkles micronutrient powder for 2 months reduces anemia among children 6 to 36 months of age in the Kyrgyz Republic: a cluster-randomized trial. Food Nutr Bull. 2010;31:446-60. | Country, Independent variable
225 | Lutter,C. K.,Rodriguez,A.,Fuenmayor,G.,Avila,L.,Sempertegui,F.,Escobar,J.. Growth and micronutrient status in children receiving a fortified complementary food. J Nutr. 2008;138:379-88. | Independent variable
226 | Luukkainen,P.,Salo,M. K.,Visakorpi,J. K.,Raiha,N. C.,Nikkari,T.. Impact of solid food on plasma arachidonic and docosahexaenoic acid status of term infants at 8 months of age. J Pediatr Gastroenterol Nutr. 1996;23:229-34. | Independent variable
227 | Luxwolda,M. F.,Kuipers,R. S.,Boersma,E. R.,van Goor,S. A.,Dijck-Brouwer,D. A.,Bos,A. F.,Muskiet,F. A.. DHA status is positively related to motor development in breastfed African and Dutch infants. Nutr Neurosci. 2014;17:97-103. | Country
228 | Majid Molla,A.,Badawi,M. H.,al-Yaish,S.,Sharma,P.,el-Salam,R. S.,Molla,A. M.. Risk factors for nutritional rickets among children in Kuwait. Pediatr Int. 2000;42:280-4. | Dependent variable
229 | Makrides,M.,Gould,J. F.,Gawlik,N. R.,Yelland,L. N.,Smithers,L. G.,Anderson,P. J.,Gibson,R. A.. Four-year follow-up of children born to women in a randomized trial of prenatal DHA supplementation. Jama. 2014;311:1802-4. | Independent variable
230 | Mamabolo,R. L.,Alberts,M.,Levitt,N. S.,Delemarre-van de Waal,H. A.,Steyn,N. P.. Association between insulin-like growth factor-1, insulin-like growth factor-binding protein-1 and leptin levels with nutritional status in 1-3-year-old children, residing in the central region of Limpopo Province, South Africa. Br J Nutr. 2007;98:762-9. | Age, Country, Independent variable
231 | Martínez Andrade,G. O.,Duque-López,M. X.,Cruz-González,M. B.,Martínez-Salgado,H.. The efect of diverse interventionist nutritional strategies aimed at diminishing anemia frequency and iron deficiency among childeren at Mexican Institute of Indigineous affairs boarding schools in the state of Hidalgo. Saludarte. 2001;2:7-21. | Age, Language
232 | Martinez,C.,Fox,T.,Eagles,J.,Fairweather-Tait,S.. Evaluation of iron bioavailability in infant weaning foods fortified with haem concentrate. J Pediatr Gastroenterol Nutr. 1998;27:419-24. | Dependent variable
233 | Matsuo,K.,Mukai,T.,Suzuki,S.,Fujieda,K.. Prevalence and risk factors of vitamin D deficiency rickets in Hokkaido, Japan. Pediatr Int. 2009;51:559-62. | Study design
234 | Mazariegos,M.,Hambidge,K. M.,Westcott,J. E.,Solomons,N. W.,Raboy,V.,Das,A.,Goco,N.,Kindem,M.,Wright,L. L.,Krebs,N. F.. Neither a zinc supplement nor phytate-reduced maize nor their combination enhance growth of 6- to 12-month-old Guatemalan infants. J Nutr. 2010;140:1041-8. | Country, Independent variable
235 | McAllister,J. C.,Lane,A. T.,Buckingham,B. A.. Vitamin D deficiency in the San Francisco Bay Area. J Pediatr Endocrinol Metab. 2006;19:205-8. | Study design
236 | Meldrum,S. J.,D’Vaz,N.,Casadio,Y.,Dunstan,J. A.,Niels Krogsgaard-Larsen,N.,Simmer,K.,Prescott,S. L.. Determinants of DHA levels in early infancy: differential effects of breast milk and direct fish oil supplementation. Prostaglandins Leukot Essent Fatty Acids. 2012;86:233-9. | Independent variable
237 | Meldrum,S. J.,D’Vaz,N.,Simmer,K.,Dunstan,J. A.,Hird,K.,Prescott,S. L.. Effects of high-dose fish oil supplementation during early infancy on neurodevelopment and language: a randomised controlled trial. Br J Nutr. 2012;108:1443-54. | Independent variable, Dependent variable
238 | Menon,P.,Bamezai,A.,Subandoro,A.,Ayoya,M. A.,Aguayo,V.. Age-appropriate infant and young child feeding practices are associated with child nutrition in India: insights from nationally representative data. Matern Child Nutr. 2015;11:73-87. | Study design, Country
239 | Merewood,A.,Mehta,S. D.,Grossman,X.,Chen,T. C.,Mathieu,J.,Holick,M. F.,Bauchner,H.. Vitamin D status among 4-month-old infants in New England: a prospective cohort study. J Hum Lact. 2012;28:159-66. | Independent variable
240 | Merhav,H.,Amitai,Y.,Palti,H.,Godfrey,S.. Tea drinking and microcytic anemia in infants. Am J Clin Nutr. 1985;41:1210-3. | Study design, Independent variable
241 | Michaelsen,K. F.. Cows’ milk in complementary feeding. Pediatrics. 2000;106:1302-3. | Study design
242 | Michaelsen,K. F.. Nutrition and growth during infancy. The Copenhagen Cohort Study. Acta Paediatr Suppl. 1997;420:1-36. | Study design
243 | Milankov,O.,Bjelica,M.,Savic,R.. What kind of milk can prevent infant’s sideropenic anemia--comparative study. Med Pregl. 2014;67:167-71. | Study design, Health Status
244 | Mira,M.,Alperstein,G.,Karr,M.,Ranmuthugala,G.,Causer,J.,Niec,A.,Lilburne,A. M.. Haem iron intake in 12-36 month old children depleted in iron: case-control study. Bmj. 1996;312:881-3. | Independent variable
245 | Mize,C. E.,Uauy,R.,Kramer,R.,Benser,M.,Allen,S.,Grundy,S. M.. Lipoprotein-cholesterol responses in healthy infants fed defined diets from ages 1 to 12 months: comparison of diets predominant in oleic acid versus linoleic acid, with parallel observations in infants fed a human milk-based diet. J Lipid Res. 1995;36:1178-87. | Independent variable, Dependent variable
246 | Monajemzadeh,S. M.,Zarkesh,M. R.. Iron deficiency anemia in infants aged 12-15 months in Ahwaz, Iran. Indian J Pathol Microbiol. 2009;52:182-4. | Study design
247 | Montalto,M. B.,Benson,J. D.,Martinez,G. A.. Nutrient intakes of formula-fed infants and infants fed cow’s milk. Pediatrics. 1985;75:343-51. | Study design
248 | Monterrosa,E. C.,Frongillo,E. A.,Vasquez-Garibay,E. M.,Romero-Velarde,E.,Casey,L. M.,Willows,N. D.. Predominant breast-feeding from birth to six months is associated with fewer gastrointestinal infections and increased risk for iron deficiency among infants. J Nutr. 2008;138:1499-504. | Independent variable
249 | Morgan,J.,Taylor,A.,Fewtrell,M.. Meat consumption is positively associated with psychomotor outcome in children up to 24 months of age. J Pediatr Gastroenterol Nutr. 2004;39:493-8. | Dependent variable
250 | Morin,K. H.. Update on what and how much infants and toddlers eat. MCN Am J Matern Child Nurs. 2006;31:269. | Study design
251 | Morley,R.,Abbott,R.,Fairweather-Tait,S.,MacFadyen,U.,Stephenson,T.,Lucas,A.. Iron fortified follow on formula from 9 to 18 months improves iron status but not development or growth: a randomised trial. Arch Dis Child. 1999;81:247-52. | Independent variable
252 | Mostert,D.,Steyn,N. P.,Temple,N. J.,Olwagen,R.. Dietary intake of pregnant women and their infants in a poor black South African community. Curationis. 2005;28:12-9. | Country, Dependent variable
253 | Moussalem,M.. Iron deficiency in newborns and infant. Revue Medicale Libanaise. 1999;11:12-16. | Language
254 | Mughal,M. Z.,Salama,H.,Greenaway,T.,Laing,I.,Mawer,E. B.. Lesson of the week: florid rickets associated with prolonged breast feeding without vitamin D supplementation. Bmj. 1999;318:39-40. | Study design
255 | Murphy,E.,Collins,M.,Gill,D.,Shortt,H.. Iron and nutritional status of toddlers. Ir Med J. 1992;85:33-4. | Study design, Age
256 | Mushaphi,L. F.,Mbhenyane,X. G.,Khoza,L. B.,Amey,A. K. A.. Infant-feeding practices of mothers and the nutritional status of infants in the Vhembe District of Limpopo Province. South African Journal of Clinical Nutrition. 2008;21:36-41. | Study design, Country
257 | Nagpal,J.,Sachdev,H. P.,Singh,T.,Mallika,V.. A randomized placebo-controlled trial of iron supplementation in breastfed young infants initiated on complementary feeding: effect on haematological status. J Health Popul Nutr. 2004;22:203-11. | Country, Independent variable
258 | Navarro,J. I.,Sigulem,D. M.,Ferraro,A. A.,Polanco,J. J.,Barros,A. J.. The double task of preventing malnutrition and overweight: a quasi-experimental community-based trial. BMC Public Health. 2013;13:212. | Independent variable, Dependent variable
259 | Nnanyelugo,D. O.. Nutritional practices and food intake measurements and their relationship to socio-economic grouping, location and their apparent nutritional adequacy in children. Appetite. 1982;3:229-41. | Study design, Country
260 | Norgate,C.. Best practice in weaning. Nurs Times. 2001;97:56-7. | Study design
261 | Ntouva,A.,Rogers,I.,MacAdam,A.,Emmett,P.. Weaning practices and iron status of exclusively breast fed infants. Journal of Human Nutrition & Dietetics. 2011;24:297-298 2p. | Study design
262 | Nube,M.,Asenso-Okyere,W. K.. Large differences in nutritional status between fully weaned and partially breast fed children beyond the age of 12 months. Eur J Clin Nutr. 1996;50:171-7. | Study design, Country
263 | Obatolu,V. A.. Growth pattern of infants fed with a mixture of extruded malted maize and cowpea. Nutrition. 2003;19:174-8. | Country, Independent variable
264 | O’Donovan,S. M.,Murray,D. M.,Hourihane,J. O.,Kenny,L. C.,Irvine,A. D.,Kiely,M.. Cohort profile: The Cork BASELINE Birth Cohort Study: Babies after SCOPE: Evaluating the Longitudinal Impact on Neurological and Nutritional Endpoints. Int J Epidemiol. 2015;44:764-75. | Study design, Dependent variable
265 | Oelofse,A.,Van Raaij,J. M.,Benade,A. J.,Dhansay,M. A.,Tolboom,J. J.,Hautvast,J. G.. The effect of a micronutrient-fortified complementary food on micronutrient status, growth and development of 6- to 12-month-old disadvantaged urban South African infants. Int J Food Sci Nutr. 2003;54:399-407. | Country
266 | Oien,T.,Storro,O.,Johnsen,R.. Do early intake of fish and fish oil protect against eczema and doctor-diagnosed asthma at 2 years of age? A cohort study. J Epidemiol Community Health. 2010;64:124-9. | Dependent variable
267 | Olmedo,S. I.,Valeggia,C.. The initiation of complementary feeding among Qom indigenous people. Arch Argent Pediatr. 2014;112:254-7. | Study design, Dependent variable
268 | Osorio,M. M.,Lira,P. I.,Ashworth,A.. Factors associated with Hb concentration in children aged 6-59 months in the State of Pernambuco, Brazil. Br J Nutr. 2004;91:307-15. | Study design
269 | Owino,V. O.,Kasonka,L. M.,Sinkala,M. M.,Wells,J. K.,Eaton,S.,Darch,T.,Coward,A.,Tomkins,A. M.,Filteau,S. M.. Fortified complementary foods with or without alpha-amylase treatment increase hemoglobin but do not reduce breast milk intake of 9-mo-old Zambian infants. Am J Clin Nutr. 2007;86:1094-103. | Study design, Country, Independent variable
270 | Palti,H.. Anemia in infancy. Public Health Rev. 2000;28:89-92. | Study design
271 | Paredes-Rojas,R. R.,Solomons,H. C.. Food for thought: impact of a supplemental nutritional program on low-income preschool children. Pediatr Nurs. 1982;8:315-7. | Age
272 | Park,J. S.,Chang,J. Y.,Hong,J.,Ko,J. S.,Seo,J. K.,Shin,S.,Lee,E. H.. Nutritional zinc status in weaning infants: association with iron deficiency, age, and growth profile. Biol Trace Elem Res. 2012;150:91-102. | Study design
273 | Pastel,R. A.,Howanitz,P. J.,Oski,F. A.. Iron sufficiency with prolonged exclusive breast-feeding in Peruvian infants. Clin Pediatr (Phila). 1981;20:625-6. | Study design
274 | Peng,L. F.,Serwint,J. R.. A comparison of breastfed children with nutritional rickets who present during and after the first year of life. Clin Pediatr (Phila). 2003;42:711-7. | Study design
275 | Persson,L. A.,Lundstrom,M.,Lonnerdal,B.,Hernell,O.. Are weaning foods causing impaired iron and zinc status in 1-year-old Swedish infants? A cohort study. Acta Paediatr. 1998;87:618-22. | Study design, Independent variable
276 | Phu,P. V.,Hoan,N. V.,Salvignol,B.,Treche,S.,Wieringa,F. T.,Khan,N. C.,Tuong,P. D.,Berger,J.. Complementary foods fortified with micronutrients prevent iron deficiency and anemia in Vietnamese infants. J Nutr. 2010;140:2241-7. | Country
277 | Pizarro,F.,Yip,R.,Dallman,P. R.,Olivares,M.,Hertrampf,E.,Walter,T.. Iron status with different infant feeding regimens: relevance to screening and prevention of iron deficiency. J Pediatr. 1991;118:687-92. | Study design
278 | Pludowski,P.,Socha,P.,Karczmarewicz,E.,Zagorecka,E.,Lukaszkiewicz,J.,Stolarczyk,A.,Piotrowska-Jastrzebska,J.,Kryskiewicz,E.,Lorenc,R. S.,Socha,J.. Vitamin D supplementation and status in infants: a prospective cohort observational study. J Pediatr Gastroenterol Nutr. 2011;53:93-9. | Independent variable
279 | Poh,Bee Koon,Ng,Boon Koon,Siti Haslinda,Mohd Din,Nik Shanita,Safii,Wong,Jyh Eiin,Budin,Siti Balkis,Ruzita,Abd Talib,Ng,Lai Oon,Khouw,Ilse,Norimah,A. Karim. Nutritional status and dietary intakes of children aged 6 months to 12 years: findings of the Nutrition Survey of Malaysian Children (SEANUTS Malaysia). British Journal of Nutrition. 2013;110:S21-35 1p. | Study design
280 | Polat,T. B.,Saz,E. U.,Urganci,N.,Akyildiz,B.,Celmeli,F.. Evaluation of iron status in relation to feeding practices in early infancy. Macedonian Journal of Medical Sciences. 2011;4:70-74. | Independent variable
281 | Pollitt,E.,Watkins,W. E.,Husaini,M. A.. Three-month nutritional supplementation in Indonesian infants and toddlers benefits memory function 8 y later. Am J Clin Nutr. 1997;66:1357-63. | Country, Dependent variable
282 | Radhakrishna,K. V.,Hemalatha,R.,Geddam,J. J.,Kumar,P. A.,Balakrishna,N.,Shatrugna,V.. Effectiveness of zinc supplementation to full term normal infants: a community based double blind, randomized, controlled, clinical trial. PLoS One. 2013;8:e61486. | Independent variable
283 | Rah,J. H.,Akhter,N.,Semba,R. D.,de Pee,S.,Bloem,M. W.,Campbell,A. A.,Moench-Pfanner,R.,Sun,K.,Badham,J.,Kraemer,K.. Low dietary diversity is a predictor of child stunting in rural Bangladesh. Eur J Clin Nutr. 2010;64:1393-8. | Study design, Country, Dependent variable
284 | Rannan-Eliya,R. P.,Hossain,S. M.,Anuranga,C.,Wickramasinghe,R.,Jayatissa,R.,Abeykoon,A. T.. Trends and determinants of childhood stunting and underweight in Sri Lanka. Ceylon Med J. 2013;58:10-8. | Study design
285 | Rao,S.,Rajpathak,V.. Breastfeeding and weaning practices in relation to nutritional status of infants. Indian Pediatr. 1992;29:1533-9. | Study design, Independent variable, Dependent variable
286 | Reghu,A.,Hosdurga,S.,Sandhu,B.,Spray,C.. Vitamin B12 deficiency presenting as oedema in infants of vegetarian mothers. Eur J Pediatr. 2005;164:257-8. | Study design
287 | Requejo,A. M.,Navia,B.,Ortega,R. M.,Lopez-Sobaler,A. M.,Quintas,E.,Gaspar,M. J.,Osorio,O.. The age at which meat is first included in the diet affects the incidence of iron deficiency and ferropenic anaemia in a group of pre-school children from Madrid. Int J Vitam Nutr Res. 1999;69:127-31. | Age
288 | Reurings,M.,Vossenaar,M.,Doak,C. M.,Solomons,N. W.. Stunting rates in infants and toddlers born in metropolitan Quetzaltenango, Guatemala. Nutrition. 2013;29:655-60. | Study design, Health Status, Dependent variable
289 | Rim,H.,Kim,S.,Sim,B.,Gang,H.,Kim,H.,Kim,Y.,Kim,R.,Yang,M.,Kim,S.. Effect of iron fortification of nursery complementary food on iron status of infants in the DPRKorea. Asia Pac J Clin Nutr. 2008;17:264-9. | Country
290 | Rivera,J. A.,Habicht,J. P.. Effect of supplementary feeding on the prevention of mild-to-moderate wasting in conditions of endemic malnutrition in Guatemala. Bull World Health Organ. 2002;80:926-32. | Country, Health Status, Independent variable, Dependent variable
291 | Rivera,J. A.,Ruel,M. T.,Santizo,M. C.,Lonnerdal,B.,Brown,K. H.. Zinc supplementation improves the growth of stunted rural Guatemalan infants. J Nutr. 1998;128:556-62. | Country, Health Status
292 | Roche,M. L.,Creed-Kanashiro,H. M.,Tuesta,I.,Kuhnlein,H. V.. Infant and young child feeding in the Peruvian Amazon: the need to promote exclusive breastfeeding and nutrient-dense traditional complementary foods. Matern Child Nutr. 2011;7:284-94. | Study design, Dependent variable
293 | Rojroongwasinkul,Nipa,Kijboonchoo,Kallaya,Wimonpeerapattana,Wanphen,Purttiponthanee,Sasiumphai,Yamborisut,Ur uwan,Boonpraderm,Atitada,Kunapan,Petcharat,Thasanasuwan,Wiyada,Khouw,Ilse. SEANUTS: the nutritional status and dietary intakes of 0.5–12-year-old Thai children. British Journal of Nutrition. 2013;110:S36-44 1p. | Study design
294 | Rosado,J. L.,Lopez,P.,Garcia,O. P.,Alatorre,J.,Alvarado,C.. Effectiveness of the nutritional supplement used in the Mexican Oportunidades programme on growth, anaemia, morbidity and cognitive development in children aged 12-24 months. Public Health Nutr. 2011;14:931-7. | Health Status, Independent variable, Dependent variable
295 | Roy,S. K.,Jolly,S. P.,Shafique,S.,Fuchs,G. J.,Mahmud,Z.,Chakraborty,B.,Roy,S.. Prevention of malnutrition among young children in rural Bangladesh by a food-health-care educational intervention: a randomized, controlled trial. Food Nutr Bull. 2007;28:375-83. | Country, Independent variable
296 | Ryan,A. S.,Martinez,G. A.,Krieger,F. W.. Feeding low-fat milk during infancy. Am J Phys Anthropol. 1987;73:539-48. | Independent variable, Dependent variable, Language
297 | Sadowitz,P. D.,Oski,F. A.. Iron status and infant feeding practices in an urban ambulatory center. Pediatrics. 1983;72:33-6. | Study design
298 | Salo,P.,Viikari,J.,Hamalainen,M.,Lapinleimu,H.,Routi,T.,Ronnemaa,T.,Seppanen,R.,Jokinen,E.,Valimaki,I.,Simell,O.. Serum cholesterol ester fatty acids in 7- and 13-month-old children in a prospective randomized trial of a low-saturated fat, low-cholesterol diet: the STRIP baby project. Special Turku coronary Risk factor Intervention Project for children. Acta Paediatr. 1999;88:505-12. | Independent variable
299 | Salvioli,G. P.,Faldella,G.,Alessandroni,R.,Lanari,M.,Di Turi,R. P.. Iron nutrition and iron status changes in Italian infants in the last decade. Ann Ist Super Sanita. 1995;31:455-9. | Study design, Independent variable
300 | Samadpour,K.,Long,K. Z.,Hayatbakhsh,R.,Marks,G. C.. Randomised comparison of the effects of Sprinkles and Foodlets with the currently recommended supplement (Drops) on micronutrient status and growth in Iranian children. Eur J Clin Nutr. 2011;65:1287-94. | Independent variable
301 | Sant’Ana,L. F. D. R.,Cruz,A. C. R. F. D.,Franceschini,S. D. C. C.,Costa,N. M. B.. Effect of a multi-mixture in the nutritional status of preschool children regarding iron. Revista de Nutricao. 2006;19:445-454. | Age
302 | Sazawal,S.,Dhingra,P.,Dhingra,U.,Gupta,S.,Iyengar,V.,Menon,V. P.,Sarkar,A.,Black,R. E.. Compliance with home-based fortification strategies for delivery of iron and zinc: its effect on haematological and growth markers among 6-24 months old children in north India. J Health Popul Nutr. 2014;32:217-26. | Country
303 | Sazawal,S.,Dhingra,U.,Dhingra,P.,Hiremath,G.,Sarkar,A.,Dutta,A.,Menon,V. P.,Black,R. E.. Micronutrient fortified milk improves iron status, anemia and growth among children 1-4 years: a double masked, randomized, controlled trial. PLoS One. 2010;5:e12167. | Age
304 | Scatliff,C. E.,Koski,K. G.,Scott,M. E.. Diarrhea and novel dietary factors emerge as predictors of serum vitamin B12 in Panamanian children. Food Nutr Bull. 2011;32:54-9. | Age
305 | Schmidt,M. K.,Muslimatun,S.,West,C. E.,Schultink,W.,Gross,R.,Hautvast,J. G.. Nutritional status and linear growth of Indonesian infants in west java are determined more by prenatal environment than by postnatal factors. J Nutr. 2002;132:2202-7. | Country, Health Status, Dependent variable
306 | Seal,A.,Kafwembe,E.,Kassim,I. A.,Hong,M.,Wesley,A.,Wood,J.,Abdalla,F.,van den Briel,T.. Maize meal fortification is associated with improved vitamin A and iron status in adolescents and reduced childhood anaemia in a food aid-dependent refugee population. Public Health Nutr. 2008;11:720-8. | Study design, Health Status
307 | Shaikh,U.,Alpert,P. T.. Nutritional rickets in Las Vegas, Nevada. J Pediatr Endocrinol Metab. 2006;19:209-12. | Study design
308 | Shamah-Levy,T.,Villalpando,S.,Rivera-Dommarco,J. A.,Mundo-Rosas,V.,Cuevas-Nasu,L.,Jimenez-Aguilar,A.. Ferrous gluconate and ferrous sulfate added to a complementary food distributed by the Mexican nutrition program Oportunidades have a comparable efficacy to reduce iron deficiency in toddlers. J Pediatr Gastroenterol Nutr. 2008;47:660-6. | Independent variable
309 | Sheng,X.,Tong,M.,Zhao,D.,Leung,T. F.,Zhang,F.,Hays,N. P.,Ge,J.,Ho,W. M.,Northington,R.,Terry,D. L.,Yao,M.. Randomized controlled trial to compare growth parameters and nutrient adequacy in children with picky eating behaviors who received nutritional counseling with or without an oral nutritional supplement. Nutr Metab Insights. 2014;7:85-94. | Age, Independent variable
310 | Shi,L.,Zhang,J.,Wang,Y.,Caulfield,L. E.,Guyer,B.. Effectiveness of an educational intervention on complementary feeding practices and growth in rural China: a cluster randomised controlled trial. Public Health Nutr. 2010;13:556-65. | Independent variable
311 | Siega-Riz,A. M.,Estrada Del Campo,Y.,Kinlaw,A.,Reinhart,G. A.,Allen,L. H.,Shahab-Ferdows,S.,Heck,J.,Suchindran,C. M.,Bentley,M. E.. Effect of supplementation with a lipid-based nutrient supplement on the micronutrient status of children aged 6-18 months living in the rural region of Intibuca, Honduras. Paediatr Perinat Epidemiol. 2014;28:245-54. | Health Status, Independent variable
312 | Siimes,M. A.,Salmenpera,L.,Perheentupa,J.. Exclusive breast-feeding for 9 months: risk of iron deficiency. J Pediatr. 1984;104:196-9. | Independent variable
313 | Silva,A. P.,Vitolo,M. R.,Zara,L. F.,Castro,C. F.. Effects of zinc supplementation on 1- to 5-year old children. J Pediatr (Rio J). 2006;82:227-31. | Independent variable, Language
314 | Simoes,E. A.,Pereira,S. M.. The growth of exclusively breastfed infants. Ann Trop Paediatr. 1986;6:17-21. | Dependent variable
315 | Siti-Noor,A. S.,Wan-Maziah,W. M.,Narazah,M. Y.,Quah,B. S.. Prevalence and risk factors for iron deficiency in Kelantanese pre-school children. Singapore Med J. 2006;47:935-9. | Study design
316 | Skau,J. K.,Touch,B.,Chhoun,C.,Chea,M.,Unni,U. S.,Makurat,J.,Filteau,S.,Wieringa,F. T.,Dijkhuizen,M. A.,Ritz,C.,Wells,J. C.,Berger,J.,Friis,H.,Michaelsen,K. F.,Roos,N.. Effects of animal source food and micronutrient fortification in complementary food products on body composition, iron status, and linear growth: a randomized trial in Cambodia. Am J Clin Nutr. 2015;101:742-51. | Country
317 | Skinner,J. D.,Carruth,B. R.,Houck,K. S.,Coletta,F.,Cotter,R.,Ott,D.,McLeod,M.. Longitudinal study of nutrient and food intakes of infants aged 2 to 24 months. J Am Diet Assoc. 1997;97:496-504. | Dependent variable
318 | Smith,A. M.,Picciano,M. F.,Deering,R. H.. Folate intake and blood concentrations of term infants. Am J Clin Nutr. 1985;41:590-8. | Independent variable
319 | Smithers,L. G.,Golley,R. K.,Brazionis,L.,Emmett,P.,Northstone,K.,Lynch,J. W.. Dietary patterns of infants and toddlers are associated with nutrient intakes. Nutrients. 2012;4:935-48. | Dependent variable
320 | Smuts,C. M.,Lombard,C. J.,Benade,A. J.,Dhansay,M. A.,Berger,J.,Hop le,T.,Lopez de Romana,G.,Untoro,J.,Karyadi,E.,Erhardt,J.,Gross,R.. Efficacy of a foodlet-based multiple micronutrient supplement for preventing growth faltering, anemia, and micronutrient deficiency of infants: the four country IRIS trial pooled data analysis. J Nutr. 2005;135:631s-638s. | Study design, Independent variable
321 | Souganidis,E. S.,Sun,K.,de Pee,S.,Kraemer,K.,Rah,J. H.,Moench-Pfanner,R.,Sari,M.,Bloem,M. W.,Semba,R. D.. Determinants of anemia clustering among mothers and children in Indonesia. J Trop Pediatr. 2012;58:170-7. | Study design, Independent variable
322 | Specker,B. L.,Ho,M. L.,Oestreich,A.,Yin,T. A.,Shui,Q. M.,Chen,X. C.,Tsang,R. C.. Prospective study of vitamin D supplementation and rickets in China. J Pediatr. 1992;120:733-9. | Study design, Independent variable
323 | Sreedhara,M. S.,Banapurmath,C. R.. A study of nutritional status of infants in relation to their complementary feeding practices. Current Pediatric Research. 2014;18:39-41. | Study design
324 | Stang,J.. Improving the eating patterns of infants and toddlers. J Am Diet Assoc. 2006;106:S7-9. | Study design
325 | Stekel,A.,Olivares,M.,Cayazzo,M.,Chadud,P.,Llaguno,S.,Pizarro,F.. Prevention of iron deficiency by milk fortification. II. A field trial with a full-fat acidified milk. Am J Clin Nutr. 1988;47:265-9. | Age, Independent variable
326 | Sultan,A. N.,Zuberi,R. W.. Late weaning: the most significant risk factor in the development of iron deficiency anaemia at 1-2 years of age. J Ayub Med Coll Abbottabad. 2003;15:3-7. | Country
327 | Tang,M.,Sheng,X. Y.,Krebs,N. F.,Hambidge,K. M.. Meat as complementary food for older breastfed infants and toddlers: a randomized, controlled trial in rural China. Food Nutr Bull. 2014;35:S188-92. | Dependent variable
328 | Thakwalakwa,C. M.,Ashorn,P.,Phuka,J. C.,Cheung,Y. B.,Briend,A.,Maleta,K. M.. Impact of lipid-based nutrient supplements and corn-soy blend on energy and nutrient intake among moderately underweight 8-18-month-old children participating in a clinical trial. Matern Child Nutr. 2014. | Independent variable, Dependent variable
329 | Thorsdottir,I.,Gunnarsson,B. S.. Dietary quality and adequacy of micronutrient intakes in children. Proc Nutr Soc. 2006;65:366-75. | Study design
330 | Torrejon,C. S.,Castillo-Duran,C.,Hertrampf,E. D.,Ruz,M.. Zinc and iron nutrition in Chilean children fed fortified milk provided by the Complementary National Food Program. Nutrition. 2004;20:177-80. | Study design
331 | Torsvik,I. K.,Markestad,T.,Ueland,P. M.,Nilsen,R. M.,Midttun,O.,Bjorke Monsen,A. L.. Evaluating iron status and the risk of anemia in young infants using erythrocyte parameters. Pediatr Res. 2013;73:214-20. | Independent variable
332 | Truswell,A. S.. ABC of nutrition. Infant feeding. Br Med J (Clin Res Ed). 1985;291:333-7. | Study design
333 | Tulchinsky,T. H.,el Ebweini,S.,Ginsberg,G. M.,Abed,Y.,Montano-Cuellar,D.,Schoenbaum,M.,Zansky,S. M.,Jacob,S.,el Tibbi,A. J.,Abu Sha’aban,D.,et al.. Growth and nutrition patterns of infants associated with a nutrition education and supplementation programme in Gaza, 1987-92. Bull World Health Organ. 1994;72:869-75. | Study design, Country
334 | Tympa-Psirropoulou,E.,Vagenas,C.,Dafni,O.,Matala,A.,Skopouli,F.. Environmental risk factors for iron deficiency anemia in children 12-24 months old in the area of Thessalia in Greece. Hippokratia. 2008;12:240-50. | Study design
335 | Ubaidullah,Masood,M. K.,Rafique,M.,Sultan,M. A.. Analysis of risk factors for vitamin D deficiency rickets in children below two years age. Pakistan Paediatric Journal. 2008;32:82-86. | Country
336 | van den Hooven,E. H.,Gharsalli,M.,Heppe,D. H.,Raat,H.,Hofman,A.,Franco,O. H.,Rivadeneira,F.,Jaddoe,V. W.. Associations of breast-feeding patterns and introduction of solid foods with childhood bone mass: The Generation R Study. Br J Nutr. 2016;115:1024-32. | Dependent variable
337 | van den Hooven,E. H.,Heppe,D. H.,Kiefte-de Jong,J. C.,Medina-Gomez,C.,Moll,H. A.,Hofman,A.,Jaddoe,V. W.,Rivadeneira,F.,Franco,O. H.. Infant dietary patterns and bone mass in childhood: the Generation R Study. Osteoporos Int. 2015;26:1595-604. | Dependent variable
338 | van Rheenen,P. F.,de Moor,L. T.,Eschbach,S.,Brabin,B. J.. A cohort study of haemoglobin and zinc protoporphyrin levels in term Zambian infants: effects of iron stores at birth, complementary food and placental malaria. Eur J Clin Nutr. 2008;62:1379-87. | Country
339 | Varea,A.,Malpeli,A.,Etchegoyen,G.,Vojkovic,M.,Disalvo,L.,Apezteguia,M.,Pereyras,S.,Pattin,J.,Ortale,S.,Carmuega,E.,Gonzalez,H. F.. Short-term evaluation of the impact of a food program on the micronutrient nutritional status of Argentinean children under the age of six. Biol Trace Elem Res. 2011;143:1337-48. | Study design, Independent variable
340 | Vazir,S.,Engle,P.,Balakrishna,N.,Griffiths,P. L.,Johnson,S. L.,Creed-Kanashiro,H.,Fernandez Rao,S.,Shroff,M. R.,Bentley,M. E.. Cluster-randomized trial on complementary and responsive feeding education to caregivers found improved dietary intake, growth and development among rural Indian toddlers. Matern Child Nutr. 2013;9:99-117. | Independent variable
341 | Vazquez-Seoane,P.,Windom,R.,Pearson,H. A.. Disappearance of iron-deficiency anemia in a high-risk infant population given supplemental iron. N Engl J Med. 1985;313:1239-40. | Study design
342 | Verma,R.,Khanna,P.,Gaur,D. R.,Meena,Prinja,S.. Assessment of nutritional status and dietary intake of pre-school children in an urban pocket. Internet Journal of Nutrition & Wellness. 2008;6:5p-5p 1p. | Study design, Age
343 | Verma,R.,Meena,Khanna,P.,Varun. Prevalence of anemia and impact of weekly iron-folic acid supplementation on school children in Urban Slums of Haryana, India. Indian Journal of Public Health Research and Development. 2012;3:147-150. | Country, Independent variable
344 | Viljakainen,H. T.,Korhonen,T.,Hytinantti,T.,Laitinen,E. K.,Andersson,S.,Makitie,O.,Lamberg-Allardt,C.. Maternal vitamin D status affects bone growth in early childhood--a prospective cohort study. Osteoporos Int. 2011;22:883-91. | Independent variable
345 | Vir,S. C.,Kalita,A.,Mondal,S.,Malik,R.. Impact of community-based mitanin programme on undernutrition in rural Chhattisgarh State, India. Food Nutr Bull. 2014;35:83-91. | Independent variable, Dependent variable
346 | Vitolo,M. R.,Bortolini,G. A.. Iron bioavailability as a protective factor against anemia among children aged 12 to 16 months. J Pediatr (Rio J). 2007;83:33-8. | Study design, Health Status, Independent variable, Language
347 | Vobecky,J. S.,Vobecky,J.,Shapcott,D.,Demers,P. P.,Blanchard,R.,Fisch,C.. The vitamin status of infants in a free living population. Int J Vitam Nutr Res. 1985;55:205-16. | Independent variable
348 | Vossenaar,M.,Solomons,N. W.. The concept of “critical nutrient density” in complementary feeding: the demands on the “family foods” for the nutrient adequacy of young Guatemalan children with continued breastfeeding. Am J Clin Nutr. 2012;95:859-66. | Dependent variable
349 | Wachs,T. D.,Creed-Kanashiro,H.,Cueto,S.,Jacoby,E.. Maternal education and intelligence predict offspring diet and nutritional status. J Nutr. 2005;135:2179-86. | Independent variable, Dependent variable
350 | Wall,C. R.,Grant,C. C.,Jones,I.. Vitamin D status of exclusively breastfed infants aged 2-3 months. Arch Dis Child. 2013;98:176-9. | Study design, Independent variable
351 | Walravens,P. A.,Chakar,A.,Mokni,R.,Denise,J.,Lemonnier,D.. Zinc supplements in breastfed infants. Lancet. 1992;340:683-5. | Independent variable
352 | Walter,T.,Pino,P.,Pizarro,F.,Lozoff,B.. Prevention of iron-deficiency anemia: comparison of high- and low-iron formulas in term healthy infants after six months of life. J Pediatr. 1998;132:635-40. | Independent variable
353 | Wandel,M.,Fagerli,R. Aa,Olsen,P. T.,Borch-Iohnsen,B.,Ek,J.. Iron status and weaning practices among Norwegian and immigrant infants. Nutrition Research. 1996;16:251-265. | Study design
354 | Wang,Y. Y.,Chen,C. M.,Wang,F. Z.,Jia,M.,Wang,K. A.. Effects of nutrient fortified complementary food supplements on anemia of infants and young children in poor rural of Gansu. Biomed Environ Sci. 2009;22:194-200. | Study design, Independent variable
355 | Wen,X.,Kong,K. L.,Eiden,R. D.,Sharma,N. N.,Xie,C.. Sociodemographic differences and infant dietary patterns. Pediatrics. 2014;134:e1387-98. | Dependent variable
356 | Wharf,S. G.,Fox,T. E.,Fairweather-Tait,S. J.,Cook,J. D.. Factors affecting iron stores in infants 4-18 months of age. Eur J Clin Nutr. 1997;51:504-9. | Study design
357 | Whitehead,R. G.. Principles involved in assessing energy, protein and micronutrient needs during infancy. Proc Nutr Soc. 1986;45:361-7. | Study design
358 | Wijaya-Erhardt,M.,Erhardt,J. G.,Untoro,J.,Karyadi,E.,Wibowo,L.,Gross,R.. Effect of daily or weekly multiple-micronutrient and iron foodlike tablets on body iron stores of Indonesian infants aged 6-12 mo: a double-blind, randomized, placebo-controlled trial. Am J Clin Nutr. 2007;86:1680-6. | Country, Independent variable
359 | Wijga,A.,Vyas,U.,Vyas,A.,Sharma,V.,Pandya,N.,Nabarro,D.. Feeding, illness and nutritional status of young children in rural Gujarat. Hum Nutr Clin Nutr. 1983;37:255-69. | Study design, Dependent variable
360 | Winick,M.. Pediatric nutrition: introduction. Pediatr Ann. 1981;10:17-8. | Study design
361 | Winkelstein,M. L.. Overfeeding in infancy: the early introduction of solid foods. Pediatr Nurs. 1984;10:205-8, 236. | Study design, Dependent variable
362 | Yip,R.,Reeves,J. D.,Lonnerdal,B.,Keen,C. L.,Dallman,P. R.. Does iron supplementation compromise zinc nutrition in healthy infants?. Am J Clin Nutr. 1985;42:683-7. | Study design, Independent variable
363 | Zhang,J.,Shi,L.,Chen,D. F.,Wang,J.,Wang,Y.. Effectiveness of an educational intervention to improve child feeding practices and growth in rural China: updated results at 18 months of age. Matern Child Nutr. 2013;9:118-29. | Dependent variable
364 | Ziegler,E. E.,Fomon,S. J.,Nelson,S. E.,Rebouche,C. J.,Edwards,B. B.,Rogers,R. R.,Lehman,L. J.. Cow milk feeding in infancy: further observations on blood loss from the gastrointestinal tract. J Pediatr. 1990;116:11-8. | Independent variable
365 | Ziegler,E. E.,Nelson,S. E.,Jeter,J. M.. Iron stores of breastfed infants during the first year of life. Nutrients. 2014;6:2023-34. | Independent variable
366 | Ziegler,E. E.,Nelson,S. E.,Jeter,J. M.. Iron supplementation of breastfed infants from an early age. Am J Clin Nutr. 2009;89:525-32. | Independent variable
367 | Ziegler,E. E.,Nelson,S. E.,Jeter,J. M.. Iron supplementation of breastfed infants. Nutr Rev. 2011;69 Suppl 1:S71-7. | Study design
368 | Ziegler,E. E.. Milks and formulas for older infants. J Pediatr. 1990;117:S76-9. | Study design, Dependent variable