# List of abbreviations

Abbreviation: Full name
BMI: Body mass index
CNPP: Center for Nutrition Policy and Promotion
CVD: Cardiovascular disease
DBP: Diastolic blood pressure
DPS: Department of Prevention Science
FNS: Food and Nutrition Service
HDI: Human development index
HDL-C: High-density lipoprotein cholesterol
HHS: Department of Health and Human Services
LDL-C: Low-density lipoprotein cholesterol
NESR: Nutrition Evidence Systematic Review
OASH: Office of the Assistant Secretary for Health
ODPHP: Office of Disease Prevention and Health Promotion
ONGA: Office of Nutrition Guidance and Analysis
PAD: Peripheral artery disease
PCS: Prospective cohort study
RCT: Randomized controlled trial
SBP: Systolic blood pressure
SSB: Sugar-sweetened beverage
TEI: Total energy intake
UK: United Kingdom
US: United States
USDA: United States Department of Agriculture