# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^xi^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 12. Added Sugars.

The systematic review described in this document updates an existing systematic review that was conducted by the 2015 Dietary Guidelines Advisory Committee with support from USDA’s Nutrition Evidence Systematic Review (NESR) team. Information about the 2015 Dietary Guidelines Advisory Committee’s review of the evidence on added sugars and risk of cardiovascular disease can be found in their report, which is available at the following website: https://nesr.usda.gov/cross-cutting-topics-public-health-importance-subcommittee.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on added sugars consumption and risk of cardiovascular disease. For this systematic review, the target populations considered were infants through older adults. The interventions or exposures considered were consumption of added sugars from foods and beverages, and their comparators were different levels of added sugars consumed (including no consumption or consumption of low- or no-calorie sweeteners). The intermediate outcomes were total cholesterol (TC), LDL cholesterol, HDL cholesterol, triglycerides, and blood pressure (systolic and diastolic) and were considered in both adults and children in experimental studies and only in children 18y and younger in observational studies. The endpoint outcomes considered were cardiovascular disease (myocardial infarction, coronary heart disease, coronary artery disease, congestive heart failure, peripheral artery disease), stroke, venous thrombosis, and cardiovascular disease-related mortality and were considered in participants 2 years or older. The key confounders for ages 2y+ were sex, age, race/ethnicity, SES, alcohol intake (in adults), physical activity, anthropometry (intermediate outcomes only), smoking, and naturally-occurring sugar intake. Other factors to be considered for ages 2y+ were total energy intake, anthropometry (health outcomes), menopausal status, medications, supplements, sodium, protein, fiber, fat, energy density, family history of CVD, and food form (solid/beverage). The key confounders for ages birth to less than 24 months were gestational age, maternal age, sex, race/ethnicity, SES (parent), parental education, feeding practices (e.g., human milk/infant formula history), and anthropometry at birth or baseline. Other factors to be considered for ages birth to less than 24 months were smoking (maternal), maternal diet, maternal anthropometry, parity, participation in a supplemental food program, family history of CVD, and completmentary feeding practices.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 7 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Study duration | - 4-week minimum for experimental studies; - No duration cutoff for observational studies | - Experimental studies <4 weeks in duration
Sample size | - Observational studies enrolling >1,000 participants | - Observational studies enrolling <1,000 participants
Intervention/exposure | Consumption of added sugars, particularly added sugars from the overall diet or from a food or beverage group that represent a large portion of overall added sugars intake, such as SSBs | Consumption of:; - Individual types of added sugars (e.g., overall honey intake, which likely does not represent overall added sugars intake); - Experimentally-manipulated foods or beverages; - Low- or no-calorie sweeteners; - Sugar alcohols
Comparator | - Different level of added sugars consumed, including no consumption or consumption of low-calorie sweeteners | - No comparator
Outcomes | [underlined: Intermediate outcomes] (Experimental studies: Ages 2y+ (Observational studies: 2-18y only):; - Total Cholesterol (TC); - LDL Cholesterol; - HDL Cholesterol; - Triglycerides; - Blood pressure (systolic and diastolic); [underlined: Health outcomes]: (Ages 2y+); - Cardiovascular disease; ○ Myocardial infarction, coronary heart disease, coronary artery disease,; ○ Congestive heart failure,; ○ Peripheral artery disease; - Stroke (ischemic & hemorrhagic separated when possible); - Venous thrombosis; - Cardiovascular disease-related mortality
Date of publication | - January 2000 to August 2014 (existing NESR systematic review); - September 2014 – September 2019 (update) | - Articles published prior to September 2014
Publication status | - Articles published in peer-reviewed journals | - Articles not published in peer-reviewed journals, including unpublished data, manuscripts, reports, abstracts, pre-prints, and conference proceedings
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^xii^ | - Studies conducted in Very High or High Human Development Countries | - Studies conducted in Medium or lower Human Development Countries
Study participants | - Human participants; - Males; - Females (including pregnant and lactating women) | - Animal subjects; - Hospitalized samples
Age of study participants | - Age at intervention or exposure:; - Infants & Toddlers (Birth-24 months); - Child (2-5 years); - Child (6-12 years); - Adolescents (13-18 years); - Adults (19-64 years); - Older adults (65+ years); - Age at outcome:; - Child (2-5 years); - Child (6-12 years); - Adolescents (13-18 years); - Adults (19-64 years); - Older adults (65+ years)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease; - Studies that exclusively enroll participants with high blood pressure or high cholesterol and are evaluating cardiovascular disease endpoint outcomes (i.e., studies that aim to prevent cardiovascular disease in participants who are at high risk; - Studies that enroll some participants with endpoint outcomes of cardiovascular disease; - Studies that enroll infants born full-term (≥37 weeks and 0/7 days gestational age) | - Studies that exclusively enroll participants diagnosed with a disease, or hospitalized with an illness or injury. (For this criterion, studies that exclusively enroll participants with obesity will not be excluded).; - Studies that exclusively enroll participants with high blood pressure or high cholesterol and are evaluating blood pressure or cholesterol outcomes (i.e., studies that aim to treat participants who already have high blood pressure or high cholesterol); - Studies that exclusively enroll participants with endpoint outcomes of cardiovascular disease (i.e., studies that aim to treat participants who have already been diagnosed with the endpoint outcomes of interest); - Studies that exclusively enroll infants born preterm (gestational age <37 weeks and 0/7 days), infants with low birth weight (<2500g), and/or infants born small for gestational age

### Electronic databases and search terms

Listed below are the databases searched to identify all potentially relevant articles that have been published to address the update to the existing systematic review.

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: October 2, 2019
- Date range searched: January 1, 2014-October 2, 2019
- Search Terms:
  - #1 - “Sweetening Agents”[Mesh] OR “Sweetening Agents”[Pharmacological Action] OR sweeten*[tiab] OR sweets[tw] OR sugary[tw] OR free sugar* OR high sugar* OR sugar substitute* OR table sugar* OR cane sugar* OR cane juice* OR sugar cane* OR sugarcane* OR sugar beet* OR corn sugar* OR sugar intake* OR sugar add* OR raw sugar* OR liquid sugar* OR invert sugar* OR sugar based* OR added sugar* OR sugar added[tw] OR brown sugar* OR white sugar* OR granulated sugar* OR powdered sugar* OR sugar coated* OR sugar sweeten* OR confectioner* OR “Dietary Sugars”[Mesh] OR dietary sugar* OR “Sugar Alcohols”[Mesh] OR sugar alcohol* OR “Nutritive Sweeteners”[Mesh] OR sucrose[tiab] OR sucralose[tw] OR maltose[tiab] OR maltodextrin[tw] OR monosaccharide[tiab] OR “Disaccharides”[Mesh] OR disaccharide[tiab] OR dextrose[tiab] OR “Molasses”[Mesh] OR molasses[tw] OR nectar* OR “Fructose”[Mesh] OR fructose[tiab] OR high-fructose[tw] OR syrup* OR “Honey”[Mesh] OR honey[tw] OR juice concentrat* OR “Lactose”[Mesh] OR lactose[tiab] OR sweetened drink* OR sweet drink* OR sugary drink* OR chocolate drink* OR flavored milk* OR flavoured milk* OR flavored water* OR flavoured water* OR “Candy”[Mesh] OR candy[tw] OR candies[tw] OR pastries[tw] OR “Ice Cream”[Mesh] OR ice cream* OR dairy dessert* OR frozen dessert* OR jello[tw] OR “Yogurt”[Mesh] OR yogurt*[tiab] OR cookies[tw] OR cake*[tw] OR pie[tw] OR pies[tw] OR caramel OR malt barley[tw] OR barley malt* OR chewing gum* OR cereal[tw] OR cereals[tw] OR fruit dessert* OR dried fruit* OR canned fruit* OR processed food* OR granola OR jellies[tiab] OR “Energy Drinks”[Mesh] OR energy drink* OR “Carbonated Beverages”[Mesh] OR carbonated beverage* OR carbonated drink* OR fruit beverage* OR fruit drink* OR fruit punch* OR fruitade* OR soda[tiab] OR soft drink* OR diet beverage* OR sports drink* OR ((“Sugars”[Mesh:noexp] OR sugar*[tiab]) AND (“Food and Beverages”[Mesh] OR beverage* OR juice* OR drink* OR food[tiab] OR foods[tiab] OR “Meals”[Mesh] OR meal[tiab] OR snack* OR breakfast* OR “Nutritive Value”[Mesh] OR consumption[tiab] OR intake[tiab]OR “Diet”[Mesh:NoExp] OR diet[tiab]))
  - #2 - “Cardiovascular Diseases”[Mesh:noexp] OR cardiovascular disease*[tiab] OR coronary artery disease[tiab] OR heart disease*[tiab] OR “Heart Failure”[Mesh] OR heart failure[tiab] OR “Myocardial Infarction”[Mesh] OR myocardial infarction*[tiab] OR “Myocardial Ischemia”[Mesh] OR Myocardial Ischemia*[tiab] OR “Stroke”[Mesh] OR stroke[tiab] OR angina[tiab] OR heart attack[tiab] OR “Venous Thrombosis”[Mesh] OR venous thrombosis[tiab] OR hypertension[tiab] OR high blood pressure[tiab] OR “Lipids/blood”[Mesh] OR “Cholesterol, HDL”[Mesh] OR HDL cholesterol[tiab] OR “Cholesterol, LDL”[Mesh] OR LDL cholesterol[tiab] OR total cholesterol[tiab] OR “Triglycerides”[Mesh] OR triglycerides[tiab]
  - #3 - (#1 AND #2)
  - #4 - (#1 AND #2) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2014/01/01 to 2019/10/02; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: October 2, 2019
- Date range searched: January 1, 2014-October 2, 2019
- Search Terms:
  - #1 - [mh “Sweetening Agents”] OR [mh “Dietary Sugars”] OR [mh “Sugar Alcohols”] OR [mh “Nutritive Sweeteners”] OR [mh Disaccharides] OR [mh Molasses] OR [mh Fructose] OR [mh Honey] OR [mh Lactose] OR [mh Candy] OR [mh “Ice Cream”] OR [mh Yogurt] OR [mh “Energy Drinks”] OR [mh “Carbonated Beverages”]
  - #2 - sweeten* OR sweets OR sugary OR “free sugar*” OR “high sugar*” OR “sugar substitute*” OR “table sugar*” OR “cane sugar*” OR “cane juice*” OR “sugar cane*” OR sugarcane* OR “sugar beet*” OR “corn sugar*” OR “sugar intake*” OOR “granulated sugar*” OR “powdered sugar*” OR “sugar coated*” OR “sugar sweeten*” OR “sugar add*” OR “raw sugar*” OR “liquid sugar*” OR “invert sugar*” OR “sugar based” OR “added sugar*” OR “sugar added” OR “brown sugar*” OR “white sugar*” OR “granulated sugar*” OR “powdered sugar*” OR “sugar coated*” OR “sugar sweeten*” OR confectioner* OR “dietary sugar*” OR “sugar alcohol*” OR sucrose OR sucralose OR maltose OR maltodextrin OR monosaccharide OR disaccharide OR dextrose OR molasses OR nectar* OR fructose OR high-fructose OR syrup* OR honey OR “juice concentrat*” OR lactose OR “sweetened drink*” OR “sweet drink*” OR “sugary drink*”“chocolate drink*” OR “flavored milk*” OR “flavoured milk*” OR “flavored water*” OR “flavoured water*” OR candy OR candies OR pastries OR “ice cream*” OR “dairy dessert*” OR “frozen dessert*” OR jello OR yogurt* OR cookies OR cake* OR pie OR pies OR caramel OR “malt barley” OR “barley malt*” OR “chewing gum*” OR cereal OR cereals OR “fruit dessert*” OR “dried fruit*” OR “canned fruit*” OR “processed food*” OR granola OR jellies OR “energy drink*” OR “carbonated beverage*” OR “carbonated drink*” OR “fruit beverage*” OR “fruit drink*” OR “fruit punch*” OR fruitade* OR soda OR “soft drink*” OR “diet beverage*” OR “sports drink*”
  - #3 - (([mh ^Sugars] OR sugar*) NEAR/6 ([mh “Food and Beverages”] OR beverage* OR juice* OR drink* OR food OR foods OR [mh Meals] OR meal OR snack* OR breakfast* OR [mh “Nutritive Value”] OR consumption OR intake OR [mh ^Diet] OR diet))
  - #4 - #1 OR #2 OR #3
  - #5 - [mh ^“Cardiovascular Diseases”] OR [mh “Heart Failure”] OR [mh “Myocardial Infarction”] OR [mh “Myocardial Ischemia”] OR [mh Stroke] OR [mh “Venous Thrombosis”] OR [mh Lipids/BL] OR [mh “Cholesterol, HDL”] OR [mh “Cholesterol, LDL”] OR [mh Triglycerides]
  - #6 - (“cardiovascular disease*” OR “coronary artery disease” OR “heart disease” OR “heart failure” OR “myocardial infarction*” OR “myocardial ischemia*” OR stroke OR angina OR “heart attack” OR “venous thrombosis” OR “hypertension” OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR triglycerides):ti,ab,kw
  - #6 - #5 OR #6
  - #7 - #4 AND #6" with Publication Year from 2014 to 2019, in Trials (Word variations have been searched)

#### Embase

- Provider: Elsevier
- Date(s) Searched: October 2, 2019
- Date range searched: January 1, 2014-October 2, 2019
- Search Terms:
  - #1 - ‘sweetening agent’/exp OR ‘sugar intake’/exp OR ‘sugar alcohol’/exp OR ‘nutritive sweetener’/exp OR ‘disaccharide’/exp OR ‘molasses’/de OR ‘fructose’/de OR ‘honey’/de OR ‘lactose’/de OR ‘candy’/de OR ‘ice cream’/de OR ‘yoghurt’/de OR ‘energy drink’/de OR ‘carbonated beverage’/de
  - #2 - sweeten*:ab,ti OR sweets:ab,ti OR sugary:ab,ti OR ‘free sugar*’:ab,ti OR ‘high sugar*’:ab,ti OR ‘sugar substitute*’:ab,ti OR ‘table sugar*’:ab,ti OR ‘cane sugar*’:ab,ti OR ‘cane juice*’:ab,ti OR ‘sugar cane*’:ab,ti OR sugarcane*:ab,ti OR ‘sugar beet*’:ab,ti OR ‘corn sugar*’:ab,ti OR ‘sugar intake*’:ab,ti OR ‘sugar add*’:ab,ti OR ‘raw sugar*’:ab,ti OR ‘liquid sugar*’:ab,ti OR ‘invert sugar*’:ab,ti OR ‘sugar based*’:ab,ti OR ‘added sugar*’:ab,ti OR ‘sugar added’:ab,ti OR ‘brown sugar*’:ab,ti OR ‘white sugar*’:ab,ti OR ‘granulated sugar*’:ab,ti OR ‘powdered sugar*’:ab,ti OR ‘sugar coated*’:ab,ti OR ‘sugar sweeten*’:ab,ti OR confectioner*:ab,ti OR ‘dietary sugar*’:ab,ti OR ‘sugar alcohol*’:ab,ti OR sucrose:ab,ti OR sucralose:ab,ti OR maltose:ab,ti OR maltodextrin:ab,ti OR monosaccharide:ab,ti OR disaccharide:ab,ti OR dextrose:ab,ti OR molasses:ab,ti OR nectar*:ab,ti OR fructose:ab,ti OR ‘high fructose’:ab,ti OR syrup*:ab,ti OR honey:ab,ti OR ‘juice concentrat*’:ab,ti OR lactose:ab,ti OR ‘sweetened drink*’:ab,ti OR ‘sweet drink*’:ab,ti OR ‘sugary drink*’:ab,ti OR ‘chocolate drink*’:ab,ti OR ‘flavored milk*’:ab,ti OR ‘flavoured milk*’:ab,ti OR ‘flavored water*’:ab,ti OR ‘flavoured water*’:ab,ti OR candy:ab,ti OR candies:ab,ti OR pastries:ab,ti OR ‘ice cream*’:ab,ti OR ‘dairy dessert*’:ab,ti OR ‘frozen dessert*’:ab,ti OR jello:ab,ti OR yogurt*:ab,ti OR cookies:ab,ti OR cake*:ab,ti OR pie:ab,ti OR pies:ab,ti OR caramel:ab,ti OR ‘malt barley’:ab,ti OR ‘barley malt*’:ab,ti OR ‘chewing gum*’:ab,ti OR cereal:ab,ti OR cereals:ab,ti OR ‘fruit dessert*’:ab,ti OR ‘dried fruit*’:ab,ti OR ‘canned fruit*’:ab,ti OR ‘processed food*’:ab,ti OR granola:ab,ti OR jellies:ab,ti OR ‘energy drink*’:ab,ti OR ‘carbonated beverage*’:ab,ti OR ‘carbonated drink*’:ab,ti OR ‘fruit beverage*’:ab,ti OR ‘fruit drink*’:ab,ti OR ‘fruit punch*’:ab,ti OR fruitade*:ab,ti OR soda:ab,ti OR ‘soft drink*’:ab,ti OR ‘diet beverage*’:ab,ti OR ‘sports drink*’:ab,ti
  - #3 - (sugar* NEAR/6 (food OR foods OR beverage* OR juice* OR drink* OR meal OR meals OR snack* OR breakfast*)
  - #4 - #1 OR #2 OR #3
  - #5 - ‘cardiovascular disease’/de OR ‘heart failure’/exp OR ‘heart infarction’/exp OR ‘heart muscle ischemia’/exp OR ‘cerebrovascular accident’/exp OR ‘vein thrombosis’/exp OR ‘high density lipoprotein cholesterol’/de OR ‘low density lipoprotein cholesterol’/de OR ‘triacylglycerol’/exp
  - #6 - ‘cardiovascular disease*’:ab,ti OR ‘coronary artery disease’:ab,ti OR ‘heart disease’:ab,ti OR ‘heart failure’:ab,ti OR ‘myocardial infarction*’:ab,ti OR ‘myocardial ischemia*’:ab,ti OR stroke:ab,ti OR angina:ab,ti OR ‘heart attack’:ab,ti OR ‘venous thrombosis’:ab,ti OR ‘hypertension’:ab,ti OR ‘high blood pressure’:ab,ti OR ‘hdl cholesterol’:ab,ti OR ‘ldl cholesterol’:ab,ti OR ‘total cholesterol’:ab,ti OR triglycerides:ab,ti
  - #7 - #5 OR #6
  - #8 - #4 AND #7
  - #9 - #4 AND #7 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2014-2019]/py NOT ([conference abstract]/lim OR [conference review]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 8 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between added sugars consumption and risk of cardiovascular disease. The literature search yielded 5,521 articles. During title screening, 4,474 articles were screened out. During abstract screening, 816 articles were screened out. During full-text screening, 208 articles were screened out. No additional articles were identified to include during the hand search. A total of 23 articles were included in the systematic review at the end of the search and screening process.

### Excluded articles

The table below lists the articles excluded after full-text screening. At least one reason for exclusion is provided for each article, which may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 8 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1 | . Correction to: Artificially sweetened beverages and stroke, coronary heart disease, and all-cause mortality in the Women’s Health Initiative. Stroke. 2019. 50:e176. doi:10.1161/str.0000000000000190. | Study design; Intervention/Exposure
2 | . No changes in uric acid or blood pressure after 6 months of daily consumption of sugar sweetened or diet beverages. J Am Soc Hypertens. 2016. Conference: 31st Annual Scientific Meeting of the American Society of Hypertension. United States. 10:e56. | Publication status
3 | Ab Wahab, SZ, Nik Hussain, NH, Zakaria, R, et al. Long-term effects of honey on cardiovascular parameters and anthropometric measurements of postmenopausal women. Complement Ther Med. 2018. 41:154-160. doi:10.1016/j.ctim.2018.08.015. | Intervention/Exposure
4 | Acosta-Navarro JC, Oki AM, Antoniazzi L, et al. Consumption of animal-based and processed food associated with cardiovascular risk factors and subclinical atherosclerosis biomarkers in men. Rev Assoc Med Bras. 2019. 65:43-50. doi:10.1590/18069282.65.1.43. | Study design; Intervention/Exposure
5 | Adriouch S, Lelong H, Kesse-Guyot E, et al. Compliance with nutritional and lifestyle recommendations in 13,000 patients with a cardiometabolic disease from the Nutrinet-Sante Study. Nutrients. 2017. 9: 546. doi:10.3390/nu9060546. | Intervention/Exposure; Outcome
6 | Al Suwaidi, J. Dietary patterns and their association with acute coronary heart disease: Lessons from the REGARDS Study. Glob Cardiol Sci Pract. 2015. 2015:56. doi:10.5339/gcsp.2015.56. | Intervention/Exposure; Publication status
7 | AlEssa HB, Cohen R, Malik VS, et al. Carbohydrate quality and quantity and risk of coronary heart disease among US women and men. Am J Clin Nutr. 2018. 107:257-267. doi:10.1093/ajcn/nqx060. | Intervention/Exposure
8 | Alvarez-Alvarez I, Toledo E, Lecea O, et al. Adherence to a priori dietary indexes and baseline prevalence of cardiovascular risk factors in the PREDIMED-Plus randomised trial. Eur J Nutr. 2019. 59(3):1219-1232. doi:10.1007/s00394-019-01982-x. | Intervention/Exposure
9 | Angelopoulos TJ, Lowndes J, Sinnett S, Rippe, JM. Fructose containing sugars at normal levels of consumption do not effect adversely components of the metabolic syndrome and risk factors for cardiovascular disease. Nutrients. 2016. 8:179. doi:10.3390/nu8040179. | Intervention/Exposure; Comparator
10 | Angelopoulos, TJ, Lowndes, J, Sinnett, S, Rippe, JM. Fructose containing sugars do not raise blood pressure or uric acid at normal levels of human consumption. J Clin Hypertens. 2015. 17:87-94. doi:10.1111/jch.12457. | Intervention/Exposure; Comparator
11 | Anil, S, Charlton, KE, Tapsell, LC, Probst, Y, Ndanuko, R, Batterham, MJ. Identification of dietary patterns associated with blood pressure in a sample of overweight Australian adults. J Hum Hypertens. 2016. 30:672-678. doi:10.1038/jhh.2016.10. | Intervention/Exposure
12 | Anjana, RM, Sudha, V, Nair, DH, et al. Diabetes in Asian Indians-how much is preventable? Ten-year follow-up of the Chennai Urban Rural Epidemiology Study (CURES-142). Diabetes Res Clin Pract. 2015. 109:253-61. doi:10.1016/j.diabres.2015.05.039. | Intervention/Exposure; Country
13 | Asadi, Z, Shafiee, M, Sadabadi, F, Heidari-Bakavoli, A, Moohebati, M, Khorrami, MS, Darroudi, S, Heidari, S, Hoori, T, Tayefi, M, Mohammadi, F, Esmaeily, H, Safarian, M, Ghayour-Mobarhan, M, Ferns, GA. Association of dietary patterns and risk of cardiovascular disease events in the MASHAD cohort study. J Hum Nutr Diet. 2019. 32(6)789-801. doi:10.1111/jhn.12669. | Intervention/Exposure
14 | Asghari, G, Yuzbashian, E, Mirmiran, P, Bahadoran, Z, Azizi, F. Prediction of metabolic syndrome by a high intake of energy-dense nutrient-poor snacks in Iranian children and adolescents. Pediatr Res. 2016. 79:697-704. doi:10.1038/pr.2015.270. | Intervention/Exposure
15 | Atkins, JL, Whincup, PH, Morris, RW, Lennon, LT, Papacosta, O, Wannamethee, SG. Dietary patterns and the risk of CVD and all-cause mortality in older British men. Br J Nutr. 2016. 116:1246-1255. doi:10.1017/s0007114516003147. | Intervention/Exposure
16 | Bahadoran, Z, Mirmiran, P, Tohidi, M, Azizi, F. Longitudinal associations of high-fructose diet with cardiovascular events and potential risk factors: Tehran Lipid and Glucose Study. Nutrients. 2017. 9(8):872. doi:10.3390/nu9080872. | Intervention/Exposure
17 | Barbalho SM, Fontana LCS, Finalli EFR, et al. Eating habits and presence of cardiovascular risks in children. Int J Adolesc Med Health. 2016. 30(2). doi:10.1515/ijamh-2016-0045. | Study design
18 | Beasley, JM, Yi, SS, Ahn, J, Kwon, SC, Wylie-Rosett, J. Dietary patterns in Chinese Americans are associated with cardiovascular disease risk factors, the Chinese American Cardiovascular Health Assessment (CHA CHA). J Immigr Minor Health. 2019. 21:1061-1069. doi:10.1007/s10903-018-0800-z. | Study design; Intervention/Exposure
19 | Bihuniak, JD, Ramos, A, Huedo-Medina, T, Hutchins-Wiese, H, Kerstetter, JE, Kenny, AM. Adherence to a Mediterranean-Style diet and its influence on cardiovascular risk factors in postmenopausal women. J Acad Nutr Diet. 2016. 116:1767-1775. doi:10.1016/j.jand.2016.06.377. | Intervention/Exposure
20 | Bonaccio, M, Di Castelnuovo, A, Costanzo, S,et al. Adherence to the traditional Mediterranean diet and mortality in subjects with diabetes. Prospective results from the MOLI-SANI study. Eur J Prev Cardiol. 2016. 23:400-7. doi:10.1177/2047487315569409. | Health status
21 | Butler, AA, St-Onge, MP, Siebert, EA, Medici, V, Stanhope, KL, Havel, PJ. Differential responses of plasma adropin concentrations to dietary glucose or fructose consumption in humans. Sci Rep. 2015. 5:14691. doi:10.1038/srep14691. | Comparator; Outcome
22 | Campos, V, Despland, C, Brandejsky, V, et al. Metabolic effects of replacing sugar-sweetened beverages with artificially-sweetened beverages in overweight subjects with or without hepatic steatosis: a randomized control clinical trial. Nutrients. 2017. 9(3):202. doi:10.3390/nu9030202. | Outcome
23 | Campos, V, Despland, C, Brandejsky, V, et al. Sugar- and artificially sweetened beverages and intrahepatic fat: A randomized controlled trial. Obesity. 2015. 23:2335-2339. doi:10.1002/oby.21310. | Outcome
24 | Campos, V, Despland, C, Schneiter, Ph, Brandejsky, V, Kreis, R, Boesch, Ch, Tappy, L. A randomized control trial of sugar-sweetened and artificially sweetened beverages and intrahepatic fat in overweight subjects. FASEB J. 2015. 29(Suppl 1):602.5. | Publication status
25 | Charkiewicz, AE, Jamiolkowski, J, Pedzinski, B, et al. Changes in dietary patterns and the nutritional status in men in the metallurgical industry in poland over a 21-year period. Ann Nutr Metab. 2018. 72:161-171. doi:10.1159/000485389. | Intervention/Exposure; Outcome
26 | Charriere, N, Montani, JP, Dulloo, AG. Acute metabolic and cardiovascular responses of healthy young adults to the ingestion of galactose-the forgotten sugar. Obesity facts. 2015. 8:114. doi:10.1159/000382140. | Publication status
27 | Cheraghi, Z, Nedjat, S, Mirmiran, P, et al. Effects of food items and related nutrients on metabolic syndrome using Bayesian multilevel modelling using the Tehran Lipid and Glucose Study (TLGS): A cohort study. BMJ Open. 2018. 8:e020642 doi:10.1136/bmjopen-2017-020642. | Study design; Intervention/Exposure; Outcome
28 | Chong, ZX, Ho, JH, Hussain, NHN, et al. The effects of Tualang honey versus honey cocktail (HC124) on physiological changes and hormonal profiles among postmenopausal women: a preliminary study. Int J Collab Res Intern Med Public Health. 2015. 7:40-51. | Intervention/Exposure; Comparator
29 | Chung S, Ha K, Lee HS, et al. Soft drink consumption is positively associated with metabolic syndrome risk factors only in Korean women: Data from the 2007-2011 Korea National Health and Nutrition Examination Survey. Metabolism. 2015. 64:1477-84. doi:10.1016/j.metabol.2015.07.012. | Study design
30 | Dale, MTG, Magnus, P, Leirgul, E, et al. Intake of sucrose-sweetened soft beverages during pregnancy and risk of congenital heart defects (CHD) in offspring: a Norwegian pregnancy cohort study. Eur J Epidemiol. 2019. 34:383-396. doi:10.1007/s10654-019-00480-y. | Outcome
31 | de Paula Franco, E, Moraes de Oliveira, GM, Raggio Luiz, R, Rosa, G. Effect of hypoenergetic diet combined with consumption of coconut flour in overweight women. Nutr Hosp. 2015. 32:2012-8. doi:10.3305/nh.2015.32.5.9661. | Intervention/Exposure
32 | Dennison, M, Sisson, SB, Stephens, L, Morris, et al. Obesogenic Behaviors and Depressive Symptoms’ Influence on Cardiometabolic Risk Factors in American Indian Children. J Allied Health. 2019. 48:100-107. | Study design; Intervention/Exposure
33 | Derakhshandeh-Rishehri, SM, Heidari-Beni, M, Feizi, A, Askari, GR, Entezari, MH. Effect of honey vinegar syrup on blood sugar and lipid profile in healthy subjects. Int J Prev Med. 2014. 5:1608-15. | Intervention/Exposure
34 | Despland, C, Walther, B, Kast, C, Campos, V, Rey, V, Stefanoni, N, Tappy, L. A randomized-controlled clinical trial of high fructose diets from either Robinia honey or free fructose and glucose in healthy normal weight males. Clin Nutr ESPEN. 2017. 19:16-22. doi:10.1016/j.clnesp.2017.01.009. | Intervention/Exposure; Study duration
35 | Dhurandhar, NV, Thomas, D. The link between dietary sugar intake and cardiovascular disease mortality: an unresolved question. JAMA. 2015. 313:959-960. doi:10.1001/jamainternmed.2013.13563. | Study design; Other; Review - article and abstract are different
36 | Dushay, JR, Toschi, E, Mitten, EK, Fisher, FM, Herman, MA, Maratos-Flier, E. Fructose ingestion acutely stimulates circulating FGF21 levels in humans. Mol Metab. 2015. 4:51-57. doi:10.1016/j.molmet.2014.09.008. | Intervention/Exposure; Study duration
37 | Dusilova, T, Kovar, J, Drobny, M, et al. Different acute effects of fructose and glucose administration on hepatic fat content. Am J Clin Nutr. 2019. 109:1519-1526. doi:10.1093/ajcn/nqy386. | Outcome; Study duration
38 | Ebbeling, CB, Feldman, HA, Steltz, SK, Ludwig, DS. Differential effects of sugar-sweetened, artificially sweetened, and unsweetened beverages on taste preference but not CVD risk factors in a 12-month RCT. Circulation. 2019. 139(Suppl 1):AP337. doi:10.1161/circ.139.suppl_1.044. | Publication status
39 | Eloranta, AM, Lindi, V, Schwab, U, et al. Dietary factors associated with metabolic risk score in Finnish children aged 6-8 years: the PANIC study. Eur J Nutr. 2014. 53:1431-9. doi:10.1007/s00394-013-0646-z. | Study design; Sample size
40 | Enginyurt, O, Cakir, L, Karatas, A, et al. The role of pure honey in the treatment of diabetes mellitus. Biomedical Research. 2017. 28:3305-3312. | Intervention/Exposure; Health status
41 | Eren, OC, Ortiz, A, Afsar, B, Covic, A, Kuwabara, M, Lanaspa, MA, Johnson, RJ, Kanbay, M. Multilayered Interplay Between Fructose and Salt in Development of Hypertension. Hypertension. 2019. 73:265-272. doi:10.1161/hypertensionaha.118.12150. | Study design; Intervention/Exposure
42 | Ericson, U, Brunkwall, L, Alves Dias, J, Drake, I, Hellstrand, S, Gullberg, B, Sonestedt, E, Nilsson, PM, Wirfält, E, Orho-Melander, M. Food patterns in relation to weight change and incidence of type 2 diabetes, coronary events and stroke in the Malmö Diet and Cancer cohort. European Journal of Nutrition. 2019. 58:1801-1814. doi:10.1007/s00394-018-1727-9. | Intervention/Exposure
43 | Esmaeili, SS, Fallahi, F, Gholami Fesharaki, M, Noormohammadi, G. A Randomized Trial on the Effect of Razavi’s Dietary Pattern on the Components of Metabolic Syndrome. Iran Red Crescent Med J. 2014. 16:e14601. doi:10.5812/ircmj.14601. | Intervention/Exposure
44 | Farakla, I, Koui, E, Arditi, J, Papageorgiou, I, Bartzeliotou, A, Papadopoulos, GE, Mantzou, A, Papathanasiou, C, Dracopoulou, M, Papastamataki, M, Moutsatsou, P, Papassotiriou, I, Chrousos, GP, Charmandari, E. Effect of honey on glucose and insulin concentrations in obese girls. European Journal of Clinical Investigation. 2019. 49. doi:10.1111/eci.13042. | Intervention/Exposure; Comparator
45 | Fedacko, J, Vargova, V, Pella, D, Singh, RB, Gupta, AK, Juneja, LR, De Meester, F, Wilson, DW. Sugar and the heart. World Heart Journal. 2014. 6:215-218. | Study design; Publication status; Other; Not primary research
46 | Fernandez-Lazaro, CI, Toledo, E, Salas-Salvado, J, Corella, D, Fito, M, Martinez, JA, Buil-Cosiales, P. PREDIMED-Plus trial: one-year changes in the quality of dietary carbohydrate intake and concurrent changes in cardiovascular risk factors. Annals of nutrition & metabolism. 2019. 75:20-21. doi:10.1159/000501441. | Publication status
47 | Ferreira-Pego, C, Babio, N, Bes-Rastrollo, M, Corella, D, Estruch, R, Ros, E, Fito, M, Serra-Majem, L, Aros, F, Fiol, M, Santos-Lozano, JM, Munoz-Bravo, C, Pinto, X, Ruiz-Canela, M, Salas-Salvado, J. Frequent Consumption of Sugar- and Artificially Sweetened Beverages and Natural and Bottled Fruit Juices Is Associated with an Increased Risk of Metabolic Syndrome in a Mediterranean Population at High Cardiovascular Disease Risk. J Nutr. 2016. 146:1528-36. doi:10.3945/jn.116.230367. | Outcome
48 | Gajda, K, Sulich, A, Hamulka, J, Bialkowska, A. Comparing diabetic with non-diabetic overweight subjects through assessing dietary intakes and key parameters of blood biochemistry and haematology. Rocz Panstw Zakl Hig. 2014. 65:133-8. | Study design; Intervention/Exposure
49 | Gallagher, C, Clifton, P, Pedersen, E, Keogh, J. Effect of fructose vs sucrose and sucralose on glucose, insulin and triglyceride levels in a solid mixed meal in healthy people. Circulation. 2015. 132. | Publication status
50 | Gardener, H, Caunca, M, Dong, C, Cheung, YK, Alperin, N, Rundek, T, Elkind, MSV, Wright, CB, Sacco, RL. Ideal Cardiovascular Health and Biomarkers of Subclinical Brain Aging: The Northern Manhattan Study. J Am Heart Assoc. 2018. 7:e009544. doi:10.1161/jaha.118.009544. | Intervention/Exposure; Outcome
51 | Gonzalez-Granda, A, Damms-Machado, A, Basrai, M, Bischoff, SC. Changes in Plasma Acylcarnitine and Lysophosphatidylcholine Levels Following a High-Fructose Diet: A Targeted Metabolomics Study in Healthy Women. Nutrients. 2018. 10. doi:10.3390/nu10091254. | Outcome; Study duration
52 | Gooding, HC, Ning, H, Gillman, MW, Shay, C, Allen, N, Goff, DC, Jr, Lloyd-Jones, D, Chiuve, S. Application of a Lifestyle-Based Tool to Estimate Premature Cardiovascular Disease Events in Young Adults: The Coronary Artery Risk Development in Young Adults (CARDIA) Study. JAMA Intern Med. 2017. 177:1354-1360. doi:10.1001/jamainternmed.2017.2922. | Intervention/Exposure
53 | Gopinath, B, Flood, VM, Kifley, A, Louie, JC, Mitchell, P. Association Between Carbohydrate Nutrition and Successful Aging Over 10 Years. J Gerontol A Biol Sci Med Sci. 2016. 71:1335-40. doi:10.1093/gerona/glw091. | Outcome
54 | Grasgruber, P, Cacek, J, Hrazdira, E, Hrebickova, S, Sebera, M. Global Correlates of Cardiovascular Risk: A Comparison of 158 Countries. Nutrients. 2018. 10. doi:10.3390/nu10040411. | Study design
55 | Guess, N, Wijesuriya, M, Vasantharajah, L, Gulliford, M, Viberti, G, Gnudi, L, Karalliedde, J. The effect of dietary changes on distinct components of the metabolic syndrome in a young Sri Lankan population at high risk of CVD. Br J Nutr. 2016. 116:719-27. doi:10.1017/s0007114516002476. | Intervention/Exposure; Outcome
56 | Han, Y, Kwon, EY, Yu, MK, Lee, SJ, Kim, HJ, Kim, SB, Kim, YH, Choi, MS. A Preliminary Study for Evaluating the Dose-Dependent Effect of d-Allulose for Fat Mass Reduction in Adult Humans: A Randomized, Double-Blind, Placebo-Controlled Trial. Nutrients. 2018. 10. doi:10.3390/nu10020160. | Intervention/Exposure
57 | Hellstrand, S, Ericson, U, Schulz, CA, Drake, I, Gullberg, B, Hedblad, B, Engstrom, G, Orho-Melander, M, Sonestedt, E. Genetic susceptibility to dyslipidemia and incidence of cardiovascular disease depending on a diet quality index in the Malmo Diet and Cancer cohort. Genes Nutr. 2016. 11:20. doi:10.1186/s12263-016-0536-0. | Intervention/Exposure
58 | Hellstrand, S, Ericson, U, Schulz, CA, Drake, I, Gullberg, B, Hedblad, B, Engström, G, Orho-Melander, M, Sonestedt, E. Genetic susceptibility to dyslipidemia and incidence of cardiovascular disease depending on a diet quality index in the Malmö diet and cancer cohort. Genes and Nutrition. 2016. 11. doi:10.1186/s12263-016-0536-0. | Intervention/Exposure
59 | Herieka, M, Faraj, TA, Erridge, C. Reduced dietary intake of pro-inflammatory Toll-like receptor stimulants favourably modifies markers of cardiometabolic risk in healthy men. Nutr Metab Cardiovasc Dis. 2016. 26:194-200. doi:10.1016/j.numecd.2015.12.001. | Intervention/Exposure; Study duration
60 | Hernandez-Cordero, S, Popkin, BM. Impact of a Water Intervention on Sugar-Sweetened Beverage Intake Substitution by Water: A Clinical Trial in Overweight and Obese Mexican Women. Ann Nutr Metab. 2015. 66 Suppl 3:22-5. doi:10.1159/000381242. | Intervention/Exposure; Comparator
61 | Hieronimus, B, Griffen, SC, Keim, NL, Bremer, AA, Berglund, L, Nakajima, K, Havel, PJ, Stanhope, KL. Effects of Fructose or Glucose on Circulating ApoCIII and Triglyceride and Cholesterol Content of Lipoprotein Subfractions in Humans. J Clin Med. 2019. 8. doi:10.3390/jcm8070913. | Intervention/Exposure; Outcome
62 | Higgins, KA, Mattes, RD. A randomized controlled trial contrasting the effects of 4 low-calorie sweeteners and sucrose on body weight in adults with overweight or obesity. American Journal of Clinical Nutrition. 2019. 109:1288-1301. doi:10.1093/ajcn/nqy381. | Outcome
63 | Hinkle, SN, Rawal, S, Bjerregaard, AA, Halldorsson, TI, Li, M, Ley, SH, Wu, J, Zhu, Y, Chen, L, Liu, A, Grunnet, LG, Rahman, ML, Kampmann, FB, Mills, JL, Olsen, SF, Zhang, C. A prospective study of artificially sweetened beverage intake and cardiometabolic health among women at high risk. Am J Clin Nutr. 2019. doi:10.1093/ajcn/nqz094. | Intervention/Exposure
64 | Hochuli, M, Aeberli, I, Weiss, A, Hersberger, M, Troxler, H, Gerber, PA, Spinas, GA, Berneis, K. Sugar-sweetened beverages with moderate amounts of fructose, but not sucrose, induce Fatty Acid synthesis in healthy young men: a randomized crossover study. J Clin Endocrinol Metab. 2014. 99:2164-72. doi:10.1210/jc.2013-3856. | Outcome; Study duration
65 | Hooshmand, F, Asghari, G, Yuzbashian, E, Mahdavi, M, Mirmiran, P, Azizi, F. Modified Healthy Eating Index and Incidence of Metabolic Syndrome in Children and Adolescents: Tehran Lipid and Glucose Study. J Pediatr. 2018. 197:134-139.e2. doi:10.1016/j.jpeds.2018.01.080. | Intervention/Exposure; Outcome
66 | Hoscan, Y, Yigit, F, Muderrisoglu, H. Adherence to Mediterranean diet and its relation with cardiovascular diseases in Turkish population. Int J Clin Exp Med. 2015. 8:2860-6. | Intervention/Exposure
67 | Hu, EA, Steffen, LM, Coresh, J, Appel, LJ, Rebholz, CM. Adherence to the Healthy Eating Index-2015 and Other Dietary Patterns May Reduce Risk of Cardiovascular Disease, Cardiovascular Mortality, and All-Cause Mortality. J Nutr. 2019. doi:10.1093/jn/nxz218. | Intervention/Exposure
68 | Huerta-Avila, EE, Ramirez-Silva, I, Torres-Sanchez, LE, Diaz-Benitez, CE, Orbe-Orihuela, YC, Lagunas-Martinez, A, Galvan-Portillo, M, Flores, M, Cruz, M, Burguete-Garcia, AI. High Relative Abundance of Lactobacillus reuteri and Fructose Intake are Associated with Adiposity and Cardiometabolic Risk Factors in Children from Mexico City. Nutrients. 2019. 11. doi:10.3390/nu11061207. | Study design; Intervention/Exposure
69 | Hur, YI, Park, H, Kang, JH, Lee, HA, Song, HJ, Lee, HJ, Kim, OH. Associations between Sugar Intake from Different Food Sources and Adiposity or Cardio-Metabolic Risk in Childhood and Adolescence: The Korean Child-Adolescent Cohort Study. Nutrients. 2015. 8. doi:10.3390/nu8010020. | Sample size
70 | Ibarra-Reynoso, LDR, Lopez-Lemus, HL, Garay-Sevilla, ME, Malacara, JM. Effect of Restriction of Foods with High Fructose Corn Syrup Content on Metabolic Indices and Fatty Liver in Obese Children. Obes Facts. 2017. 10:332-340. doi:10.1159/000476069. | Study design; Intervention/Exposure; Outcome
71 | Iff, S, Wong, G, Webster, AC, Flood, V, Wang, JJ, Mitchell, P, Craig, JC. Relative energy balance, CKD, and risk of cardiovascular and all-cause mortality. Am J Kidney Dis. 2014. 63:437-45. doi:10.1053/j.ajkd.2013.08.026. | Intervention/Exposure
72 | Jayadi, Y, Thaha, AR, Hadju, V, Bukhari, A, Dewi, NU, Bohari, . The potential of Indonesian honey to change the lipid profiles of individuals with central obesity. Pakistan Journal of Nutrition. 2019. 18:508-513. doi:10.3923/pjn.2019.508.513. | Intervention/Exposure
73 | Jensen, PN, Howard, BV, Best, LG, O’Leary, M, Devereux, RB, Cole, SA, MacCluer, JW, Ali, T, Lee, ET, Yeh, FL, Yeh, J, Umans, JG, Fretts, AM. Associations of diet soda and non-caloric artificial sweetener use with markers of glucose and insulin homeostasis and incident diabetes: the Strong Heart Family Study. Eur J Clin Nutr. 2019. doi:10.1038/s41430-019-0461-6. | Intervention/Exposure; Outcome
74 | Jin, R, Welsh, JA, Le, NA, Holzberg, J, Sharma, P, Martin, DR, Vos, MB. Dietary fructose reduction improves markers of cardiovascular disease risk in Hispanic-American adolescents with NAFLD. Nutrients. 2014. 6:3187-201. doi:10.3390/nu6083187. | Intervention/Exposure; Health status
75 | Jin, Y, Kanaya, AM, Kandula, NR, Rodriguez, LA, Talegawkar, SA. Vegetarian Diets Are Associated with Selected Cardiometabolic Risk Factors among Middle-Older Aged South Asians in the United States. J Nutr. 2018. 148:1954-1960. doi:10.1093/jn/nxy217. | Intervention/Exposure
76 | Julian-Almarcegui, C, Vandevijvere, S, Gottrand, F, Beghin, L, Dallongeville, J, Sjostrom, M, Leclercq, C, Manios, Y, Widhalm, K, Ferreira De Morares, AC, Gonzalez-Gross, M, Stehle, P, Castillo, MJ, Moreno, LA, Kersting, M, Vyncke, K, De Henauw, S, Huybrechts, I. Association of heart rate and blood pressure among European adolescents with usual food consumption: The HELENA study. Nutr Metab Cardiovasc Dis. 2016. 26:541-8. doi:10.1016/j.numecd.2016.01.014. | Study design; Intervention/Exposure
77 | Jurado-Fasoli, L, De-la, OA, Castillo, MJ, Amaro-Gahete, FJ. Dietary differences between metabolically healthy overweight-obese and metabolically unhealthy overweight-obese adults. Br J Nutr. 2019. 1-21. doi:10.1017/s0007114519002071. | Study design; Intervention/Exposure
78 | Kang, Y, Kim, J. Soft drink consumption is associated with increased incidence of the metabolic syndrome only in women. Br J Nutr. 2017. 117:315-324. doi:10.1017/s0007114517000046. | Outcome
79 | Kaplon, RE, Hill, SD, Bispham, NZ, Santos-Parker, JR, Nowlan, MJ, Snyder, LL, Chonchol, M, LaRocca, TJ, McQueen, MB, Seals, DR. Oral trehalose supplementation improves resistance artery endothelial function in healthy middle-aged and older adults. Aging (Albany NY). 2016. 8:1167-83. doi:10.18632/aging.100962. | Comparator
80 | Karimi, G, Azadbakht, L, Haghighatdoost, F, Esmaillzadeh, A. Low energy density diet, weight loss maintenance, and risk of cardiovascular disease following a recent weight reduction program: A randomized control trial. J Res Med Sci. 2016. 21:32. doi:10.4103/1735-1995.181992. | Intervention/Exposure
81 | Kassi, EN, Landis, G, Pavlaki, A, Lambrou, G, Mantzou, E, Androulakis, I, Giannakou, A, Papanikolaou, E, Chrousos, GP. Long-term effects of stevia rebaudiana on glucose and lipid profile, adipocytokines, markers of inflammation and oxidation status in patients with metabolic syndrome. Endocrine reviews. 2016. 37. doi:10.1210/endo-meetings.2016.CE.5.SUN-577. | Publication status
82 | Katsa, ME, Ioannidis, A, Zyga, S, Tsironi, M, Koutsovitis, P, Chatzipanagiotou, S, Panagiotakos, D, Sachlas, A, Kolovos, P, Routsi, K, Pistikou, AM, Kougioumtzi Dimoliani, DE, Rojas Gil, AP. The Effect of Nutrition and Sleep Habits on Predisposition for Metabolic Syndrome in Greek Children. J Pediatr Nurs. 2018. 40:e2-e8. doi:10.1016/j.pedn.2018.01.012. | Study design; Intervention/Exposure
83 | Keller, AC. Sugar-sweetened beverages and cardiovascular diseases. Eur Heart J. 2014. 35:2203-4. | Study design
84 | Keller, J, Kahlhofer, J, Peter, A, Bosy-Westphal, A. Effects of Low versus High Glycemic Index Sugar-Sweetened Beverages on Postprandial Vasodilatation and Inactivity-Induced Impairment of Glucose Metabolism in Healthy Men. Nutrients. 2016. 8. doi:10.3390/nu8120802. | Intervention/Exposure; Outcome
85 | Khayyatzadeh, SS, Moohebati, M, Mazidi, M, Avan, A, Tayefi, M, Parizadeh, SM, Ebrahimi, M, Heidari-Bakavoli, A, Azarpazhooh, MR, Esmaily, H, Ferns, GA, Nematy, M, Safarian, M, Ghayour-Mobarhan, M. Nutrient patterns and their relationship to metabolic syndrome in Iranian adults. Eur J Clin Invest. 2016. 46:840-52. doi:10.1111/eci.12666. | Study design; Intervention/Exposure
86 | Kong, LC, Holmes, BA, Cotillard, A, Habi-Rachedi, F, Brazeilles, R, Gougis, S, Gausseres, N, Cani, PD, Fellahi, S, Bastard, JP, Kennedy, SP, Dore, J, Ehrlich, SD, Zucker, JD, Rizkalla, SW, Clement, K. Dietary patterns differently associate with inflammation and gut microbiota in overweight and obese subjects. PLoS One. 2014. 9:e109434. doi:10.1371/journal.pone.0109434. | Intervention/Exposure; Outcome
87 | Kromhout, D, Menotti, A, Alberti-Fidanza, A, Puddu, PE, Hollman, P, Kafatos, A, Tolonen, H, Adachi, H, Jacobs, DR, Jr. Comparative ecologic relationships of saturated fat, sucrose, food groups, and a Mediterranean food pattern score to 50-year coronary heart disease mortality rates among 16 cohorts of the Seven Countries Study. Eur J Clin Nutr. 2018. 72:1103-1110. doi:10.1038/s41430-018-0183-1. | Study design
88 | Kulezic, A, Bergwall, S, Fatemi, S, Sonestedt, E, Zarrouk, M, Gottsäter, A, Acosta, S. Healthy diet and fiber intake are associated with decreased risk of incident symptomatic peripheral artery disease – A prospective cohort study. Vascular Medicine (United Kingdom). 2019. doi:10.1177/1358863X19867393. | Duplicate; Other; Duplicate of ref 7287
89 | Kuzma, J, Cromer, G, Hagman, D, Breymeyer, K, Roth, C, Foster-Schubert, K, Holte, S, Weigle, D, Kratz, M. No differential effect of beverages sweetened with fructose, high-fructose corn syrup, or glucose on systemic inflammation in healthy, normal weight or obese individuals: a randomized controlled trial. FASEB journal. 2016. 30. | Publication status
90 | Kuzma, JN, Cromer, G, Hagman, DK, Breymeyer, KL, Roth, CL, Foster-Schubert, KE, Holte, SE, Weigle, DS, Kratz, M. No differential effect of beverages sweetened with fructose, high-fructose corn syrup, or glucose on systemic or adipose tissue inflammation in normal-weight to obese adults: a randomized controlled trial. Am J Clin Nutr. 2016. 104:306-14. doi:10.3945/ajcn.115.129650. | Outcome; Study duration
91 | Kwak, JH, Jo, G, Chung, HK, Shin, MJ. Association between sugar-sweetened beverage consumption and incident hypertension in Korean adults: a prospective study. Eur J Nutr. 2019. 58:1009-1017. doi:10.1007/s00394-018-1617-1. | Outcome
92 | Laclaustra, M, Rodriguez-Artalejo, F, Guallar-Castillon, P, Banegas, JR, Graciani, A, Garcia-Esquinas, E, Ordovas, J, Lopez-Garcia, E. Prospective association between added sugars and frailty in older adults. Am J Clin Nutr. 2018. 107:772-779. doi:10.1093/ajcn/nqy028. | Outcome
93 | Lara, KM, Levitan, EB, Gutierrez, OM, Shikany, JM, Safford, MM, Judd, SE, Rosenson, RS. Dietary Patterns and Incident Heart Failure in U.S. Adults Without Known Coronary Disease. J Am Coll Cardiol. 2019. 73:2036-2045. doi:10.1016/j.jacc.2019.01.067. | Intervention/Exposure
94 | Larsson, SC, Akesson, A, Wolk, A. Sweetened beverage consumption is associated with increased risk of stroke in women and men. J Nutr. 2014. 144:856-60. doi:10.3945/jn.114.190546. | Date
95 | Larsson, SC, Wolk, A, Back, M. Dietary patterns, food groups, and incidence of aortic valve stenosis: A prospective cohort study. Int J Cardiol. 2019. 283:184-188. doi:10.1016/j.ijcard.2018.11.007. | Intervention/Exposure; Comparator
96 | Leermakers, ETM, Tielemans, MJ, van den Broek, M, Jaddoe, VWV, Franco, OH, Kiefte-de Jong, JC. Maternal dietary patterns during pregnancy and offspring cardiometabolic health at age 6 years: The generation R study. Clin Nutr. 2017. 36:477-484. doi:10.1016/j.clnu.2015.12.017. | Intervention/Exposure; Population
97 | Li, Y, Hruby, A, Bernstein, AM, Ley, SH, Wang, DD, Chiuve, SE, Sampson, L, Rexrode, KM, Rimm, EB, Willett, WC, Hu, FB. Saturated Fats Compared With Unsaturated Fats and Sources of Carbohydrates in Relation to Risk of Coronary Heart Disease: A Prospective Cohort Study. J Am Coll Cardiol. 2015. 66:1538-1548. doi:10.1016/j.jacc.2015.07.055. | Intervention/Exposure
98 | Li, Y, Wang, DD, Ley, SH, Vasanti, M, Howard, AG, He, Y, Hu, FB. Time Trends of Dietary and Lifestyle Factors and Their Potential Impact on Diabetes Burden in China. Diabetes Care. 2017. 40:1685-1694. doi:10.2337/dc17-0571. | Outcome
99 | Lieffers, JRL, Ekwaru, JP, Ohinmaa, A, Veugelers, PJ. The economic burden of not meeting food recommendations in Canada: The cost of doing nothing. PLoS One. 2018. 13:e0196333. doi:10.1371/journal.pone.0196333. | Outcome
100 | Lin, WT, Lee, CY, Tsai, S, Huang, HL, Wu, PW, Chin, YT, Seal, DW, Chen, T, Chao, YY, Lee, CH. Clustering of Metabolic Risk Components and Associated Lifestyle Factors: A Nationwide Adolescent Study in Taiwan. Nutrients. 2019. 11. doi:10.3390/nu11030584. | Study design
101 | Loh, DA, Moy, FM, Zaharan, NL, Jalaludin, MY, Mohamed, Z. Sugar-sweetened beverage intake and its associations with cardiometabolic risks among adolescents. Pediatr Obes. 2017. 12:e1-e5. doi:10.1111/ijpo.12108. | Study design
102 | Lowndes, J, Sinnett, S, Pardo, S, Nguyen, VT, Melanson, KJ, Yu, Z, Lowther, BE, Rippe, JM. The effect of normally consumed amounts of sucrose or high fructose corn syrup on lipid profiles, body composition and related parameters in overweight/obese subjects. Nutrients. 2014. 6:1128-44. doi:10.3390/nu6031128. | Intervention/Exposure
103 | Lowndes, J, Sinnett, S, Yu, Z, Rippe, J. The effects of fructose-containing sugars on weight, body composition and cardiometabolic risk factors when consumed at up to the 90th percentile population consumption level for fructose. Nutrients. 2014. 6:3153-68. doi:10.3390/nu6083153. | Intervention/Exposure
104 | Macedo, RCO, Boeno, FP, Farinha, JB, Ramis, TR, Rodrigues-Krause, J, Vieira, AF, Queiroz, J, Moritz, CEJ, Reischak-Oliveira, A. Acute and residual effects of aerobic exercise on fructose-induced postprandial lipemia on lean male subjects. Eur J Nutr. 2019. 58:2293-2303. doi:10.1007/s00394-018-1780-4. | Intervention/Exposure; Outcome; Study duration
105 | Macedo, RCO, Boeno, FP, Farinha, JB, Ramis, TR, Rodrigues-Krause, J, Vieira, AF, Queiroz, J, Moritz, CEJ, Reischak-Oliveira, A. Acute and residual effects of aerobic exercise on fructose-induced postprandial lipemia on lean male subjects. European journal of nutrition. 2018. . doi:10.1007/s00394-018-1780-4. | Intervention/Exposure; Comparator
106 | Mager, DR, Iniguez, IR, Gilmour, S, Yap, J. The effect of a low fructose and low glycemic index/load (FRAGILE) dietary intervention on indices of liver function, cardiometabolic risk factors, and body composition in children and adolescents with nonalcoholic fatty liver disease (NAFLD). JPEN J Parenter Enteral Nutr. 2015. 39:73-84. doi:10.1177/0148607113501201. | Health status
107 | Maki, KC, Nieman, KM, Schild, AL, Kaden, VN, Lawless, AL, Kelley, KM, Rains, TM. Sugar-sweetened product consumption alters glucose homeostasis compared with dairy product consumption in men and women at risk of type 2 diabetes mellitus. J Nutr. 2015. 145:459-66. doi:10.3945/jn.114.204503. | Intervention/Exposure; Comparator
108 | Maki, KC, Phillips, AK. Dietary substitutions for refined carbohydrate that show promise for reducing risk of type 2 diabetes in men and women. Journal of Nutrition. 2015. 145:159S-163S. doi:10.3945/jn.114.195149. | Study design; Intervention/Exposure
109 | Mandalazi, E, Drake, I, Wirfält, E, Orho-Melander, M, Sonestedt, E. A high diet quality based on dietary recommendations is not associated with lower incidence of type 2 diabetes in the malmö diet and cancer cohort. International Journal of Molecular Sciences. 2016. 17. doi:10.3390/ijms17060901. | Intervention/Exposure; Outcome
110 | Martin, CL, Siega-Riz, AM, Sotres-Alvarez, D, Robinson, WR, Daniels, JL, Perrin, EM, Stuebe, AM. Maternal Dietary Patterns are Associated with Lower Levels of Cardiometabolic Markers during Pregnancy. Paediatr Perinat Epidemiol. 2016. 30:246-55. doi:10.1111/ppe.12279. | Intervention/Exposure
111 | Maruyama, C, Nakano, R, Shima, M, Mae, A, Shijo, Y, Nakamura, E, Okabe, Y, Park, S, Kameyama, N, Hirai, S, Nakanishi, M, Uchida, K, Nishiyama, H. Effects of a Japan Diet Intake Program on Metabolic Parameters in Middle-Aged Men. J Atheroscler Thromb. 2017. 24:393-401. doi:10.5551/jat.36780. | Intervention/Exposure
112 | Matikainen, N, Soderlund, S, Bjornson, E, Bogl, LH, Pietilainen, KH, Hakkarainen, A, Lundbom, N, Eliasson, B, Rasanen, SM, Rivellese, A, Patti, L, Prinster, A, Riccardi, G, Despres, JP, Almeras, N, Holst, JJ, Deacon, CF, Boren, J, Taskinen, MR. Fructose intervention for 12 weeks does not impair glycemic control or incretin hormone responses during oral glucose or mixed meal tests in obese men. Nutr Metab Cardiovasc Dis. 2017. 27:534-542. doi:10.1016/j.numecd.2017.03.003. | Study design; Intervention/Exposure; Comparator
113 | Matthews, LA, Rovio, SP, Jaakkola, JM, Niinikoski, H, Lagstrom, H, Jula, A, Viikari, JSA, Ronnemaa, T, Simell, O, Raitakari, OT, Pahkala, K. Longitudinal effect of 20-year infancy-onset dietary intervention on food consumption and nutrient intake: the randomized controlled STRIP study. Eur J Clin Nutr. 2019. 73:937-949. doi:10.1038/s41430-018-0350-4. | Outcome
114 | Meier, T, Gräfe, K, Senn, F, Sur, P, Stangl, GI, Dawczynski, C, März, W, Kleber, ME, Lorkowski, S. Cardiovascular mortality attributable to dietary risk factors in 51 countries in the WHO European Region from 1990 to 2016: a systematic analysis of the Global Burden of Disease Study. European Journal of Epidemiology. 2019. 34:37-55. doi:10.1007/s10654-018-0473-x. | Study design; Intervention/Exposure
115 | Mellendick, K, Shanahan, L, Wideman, L, Calkins, S, Keane, S, Lovelady, C. Diets Rich in Fruits and Vegetables Are Associated with Lower Cardiovascular Disease Risk in Adolescents. Nutrients. 2018. 10. doi:10.3390/nu10020136. | Study design; Outcome
116 | Meng, H, Matthan, NR, Benitez, SB, Fried, SK, Lichtenstein, AH. Effect of dietary carbohydrate type on serum lipid profile, adipose tissue macrophage infiltration and inflammatory status, and peripheral macrophage cholesterol efflux. Circulation. 2018. 137. | Publication status
117 | Mertens, E, Markey, O, Geleijnse, JM, Givens, DI, Lovegrove, JA. Dietary Patterns in Relation to Cardiovascular Disease Incidence and Risk Markers in a Middle-Aged British Male Population: Data from the Caerphilly Prospective Study. Nutrients. 2017. 9. doi:10.3390/nu9010075. | Intervention/Exposure
118 | Mirmiran, P, Yuzbashian, E, Asghari, G, Hosseinpour-Niazi, S, Azizi, F. Consumption of sugar sweetened beverage is associated with incidence of metabolic syndrome in Tehranian children and adolescents. Nutr Metab (Lond). 2015. 12:25. doi:10.1186/s12986-015-0021-6. | Sample size
119 | Monge, A, Lajous, M, Ortiz-Panozo, E, Rodríguez, BL, Góngora, JJ, López-Ridaura, R. Western and Modern Mexican dietary patterns are directly associated with incident hypertension in Mexican women: A prospective follow-up study. Nutrition Journal. 2018. 17. doi:10.1186/s12937-018-0332-3. | Study design; Intervention/Exposure; Outcome
120 | Moreira, PV, Hyseni, L, Moubarac, JC, Martins, APB, Baraldi, LG, Capewell, S, O’Flaherty, M, Guzman-Castillo, M. Effects of reducing processed culinary ingredients and ultra-processed foods in the Brazilian diet: a cardiovascular modelling study. Public Health Nutr. 2018. 21:181-188. doi:10.1017/s1368980017002063. | Study design; Intervention/Exposure
121 | Mousavi, SM, Milajerdi, A, Pouraram, H, Saadatnia, M, Shakeri, F, Keshteli, AH, Tan, SC, Esmaillzadeh, A. Adherence to Alternative Healthy Eating Index (AHEI-2010) is not associated with risk of stroke in Iranian adults: a case-control study. Int J Vitam Nutr Res. 2019. 1-8. doi:10.1024/0300-9831/a000603. | Study design; Intervention/Exposure
122 | Mustafa, N, Abd Majid, H, Toumpakari, Z, Carroll, HA, Yazid Jalaludin, M, Al Sadat, N, Johnson, L. The Association of Breakfast Frequency and Cardiovascular Disease (CVD) Risk Factors among Adolescents in Malaysia. Nutrients. 2019. 11. doi:10.3390/nu11050973. | Study design; Intervention/Exposure
123 | Mytton, OT, Forouhi, NG, Scarborough, P, Lentjes, M, Luben, R, Rayner, M, Khaw, KT, Wareham, NJ, Monsivais, P. Association between intake of less-healthy foods defined by the United Kingdom’s nutrient profile model and cardiovascular disease: A population-based cohort study. PLoS Med. 2018. 15:e1002484. doi:10.1371/journal.pmed.1002484. | Intervention/Exposure
124 | Nazari, SSH, Mokhayeri, Y, Mansournia, MA, Khodakarim, S, Soori, H. Associations between dietary risk factors and ischemic stroke: a comparison of regression methods using data from the Multi-Ethnic Study of Atherosclerosis. Epidemiol Health. 2018. 40:e2018021. doi:10.4178/epih.e2018021. | Intervention/Exposure
125 | Nazeminezhad, R, Tajfard, M, Latiff, LA, Mouhebati, M, Esmaeily, H, Ferns, GA, Ghayour-Mobarhan, M, Rahimi, HR. Dietary intake of patients with angiographically defined coronary artery disease and that of healthy controls in Iran. Eur J Clin Nutr. 2014. 68:109-13. doi:10.1038/ejcn.2013.205. | Study design; Intervention/Exposure
126 | Ndanuko, R, Tapsell, L, Charlton, K, Neale, E, Batterham, M. Dietary patterns associated with blood pressure in a clinical sample of overweight adults volunteering for a weight loss trial. Revista espanola de nutricion humana y dietetica. 2016. 20:460-461. | Publication status
127 | Nickols-Richardson, SM, Piehowski, KE, Metzgar, CJ, Miller, DL, Preston, AG. Changes in body weight, blood pressure and selected metabolic biomarkers with an energy-restricted diet including twice daily sweet snacks and once daily sugar-free beverage. Nutr Res Pract. 2014. 8:695-704. doi:10.4162/nrp.2014.8.6.695. | Intervention/Exposure; Comparator
128 | Nobbs, HM, Yaxley, A, Thomas, J, Delaney, C, Koczwara, B, Luszcz, M, Miller, M. Do dietary patterns in older age influence the development of cancer and cardiovascular disease: A longitudinal study of ageing. Clin Nutr. 2016. 35:528-535. doi:10.1016/j.clnu.2015.04.003. | Intervention/Exposure
129 | Nobili, V, Mosca, A, De Vito, R, Raponi, M, Scorletti, E, Byrne, CD. Liver zonation in children with non-alcoholic fatty liver disease: Associations with dietary fructose and uric acid concentrations. Liver International. 2018. 38:1102-1109. doi:10.1111/liv.13661. | Health status
130 | Novotny, JA, Baer, DJ, Khoo, C, Gebauer, SK, Charron, CS. Cranberry juice consumption lowers markers of cardiometabolic risk, including blood pressure and circulating C-reactive protein, triglyceride, and glucose concentrations in adults. J Nutr. 2015. 145:1185-93. doi:10.3945/jn.114.203190. | Intervention/Exposure
131 | Olofsson, C, Anderstam, B, Bragfors-Helin, AC, Eriksson, M, Qureshi, AR, Lindholm, B, Hilding, A, Wiczkowski, W, Orsini, N, Stenvinkel, P, Rajamand Ekberg, N. Effects of acute fructose loading on levels of serum uric acid-a pilot study. Eur J Clin Invest. 2019. 49:e13040. doi:10.1111/eci.13040. | Outcome; Study duration
132 | O’Neil, CE, Nicklas, TA, Liu, Y, Berenson, GS. Candy consumption in childhood is not predictive of weight, adiposity measures or cardiovascular risk factors in young adults: the Bogalusa Heart Study. J Hum Nutr Diet. 2015. 28 Suppl 2:59-69. doi:10.1111/jhn.12200. | Sample size
133 | Padilla-Camberos, E, Barragan-Alvarez, CP, Diaz-Martinez, NE, Rathod, V, Flores-Fernandez, JM. Effects of Agave fructans (Agave tequilana Weber var. azul) on Body Fat and Serum Lipids in Obesity. Plant Foods Hum Nutr. 2018. 73:34-39. doi:10.1007/s11130-018-0654-5. | Intervention/Exposure
134 | Papoutsou, S, Briassoulis, G, Hadjigeorgiou, C, Savva, SC, Solea, T, Hebestreit, A, Pala, V, Sieri, S, Kourides, Y, Kafatos, A, Tornaritis, M. The combination of daily breakfast consumption and optimal breakfast choices in childhood is an important public health message. Int J Food Sci Nutr. 2014. 65:273-9. doi:10.3109/09637486.2013.854750. | Intervention/Exposure
135 | Parnell, JA, Klancic, T, Reimer, RA. Oligofructose decreases serum lipopolysaccharide and plasminogen activator inhibitor-1 in adults with overweight/obesity. Obesity (Silver Spring). 2017. 25:510-513. doi:10.1002/oby.21763. | Intervention/Exposure; Outcome
136 | Pase, MP, Grima, N, Cockerell, R, Pipingas, A. Habitual intake of fruit juice predicts central blood pressure. Appetite. 2015. 84:68-72. doi:10.1016/j.appet.2014.09.019. | Study design; Intervention/Exposure
137 | Patel, L, Alicandro, G, La Vecchia, C. Low-Calorie Beverage Consumption, Diet Quality and Cardiometabolic Risk Factors in British Adults. Nutrients. 2018. 10. doi:10.3390/nu10091261. | Study design; Intervention/Exposure
138 | Payab, M, Kelishadi, R, Qorbani, M, Motlagh, ME, Ranjbar, SH, Ardalan, G, Zahedi, H, Chinian, M, Asayesh, H, Larijani, B, Heshmat, R. Association of junk food consumption with high blood pressure and obesity in Iranian children and adolescents: the CASPIAN-IV Study. J Pediatr (Rio J). 2015. 91:196-205. doi:10.1016/j.jped.2014.07.006. | Study design; Intervention/Exposure
139 | Perez-Heras, A, Ros, E, Serra-Mir, M, Vinyas, C, Mestre, C, Alegret, M, Laguna, JC. Intake of simple sugar-S from sweetened beverages is associated with cancer incidence and mortality in the predimed study cohort. Revista espanola de nutricion humana y dietetica. 2016. 20:425-426. | Publication status
140 | Price, CA, Argueta, DA, Medici, V, Bremer, AA, Lee, V, Nunez, MV, Chen, GX, Keim, NL, Havel, PJ, Stanhope, KL, DiPatrizio, NV. Plasma fatty acid ethanolamides are associated with postprandial triglycerides, ApoCIII, and ApoE in humans consuming a high-fructose corn syrup-sweetened beverage. Am J Physiol Endocrinol Metab. 2018. 315:E141-e149. doi:10.1152/ajpendo.00406.2017. | Outcome; Study duration
141 | Raatz, SK, Johnson, LK, Picklo, MJ. Consumption of Honey, Sucrose, and High-Fructose Corn Syrup Produces Similar Metabolic Effects in Glucose-Tolerant and -Intolerant Individuals. J Nutr. 2015. 145:2265-72. doi:10.3945/jn.115.218016. | Intervention/Exposure; Comparator; Study duration
142 | Ramírez-Vélez, R, Ojeda, ML, Tordecilla, MA, Peña, JC, Meneses, JF. Regular consumption of sugar-sweetened beverages increases the lipid-metabolic profile and adiposity among university students from Colombia. Revista Colombiana de Cardiologia. 2016. 23:11-18. doi:10.1016/j.rccar.2015.04.006. | Study design
143 | Rasad, H, Entezari, MH, Ghadiri, E, Mahaki, B, Pahlavani, N. The effect of honey consumption compared with sucrose on lipid profile in young healthy subjects (randomized clinical trial). Clin Nutr ESPEN. 2018. 26:8-12. doi:10.1016/j.clnesp.2018.04.016. | Intervention/Exposure
144 | Rashid, MR, Nor Aripin, KN, Syed Mohideen, FB, Baharom, N, Omar, K, Md Taujuddin, NMS, Mohd Yusof, HH, Addnan, FH. The Effect of Kelulut Honey on Fasting Blood Glucose and Metabolic Parameters in Patients with Impaired Fasting Glucose. J Nutr Metab. 2019. 2019:3176018. doi:10.1155/2019/3176018. | Intervention/Exposure
145 | Rauber, F, Campagnolo, PD, Hoffman, DJ, Vitolo, MR. Consumption of ultra-processed food products and its effects on children’s lipid profiles: a longitudinal study. Nutr Metab Cardiovasc Dis. 2015. 25:116-22. doi:10.1016/j.numecd.2014.08.001. | Intervention/Exposure
146 | Rebholz, CM, Young, BA, Katz, R, Tucker, KL, Carithers, TC, Norwood, AF, Correa, A. Patterns of Beverages Consumed and Risk of Incident Kidney Disease. Clin J Am Soc Nephrol. 2019. 14:49-56. doi:10.2215/cjn.06380518. | Outcome
147 | Rezende, LF, Azeredo, CM, Canella, DS, Luiz Odo, C, Levy, RB, Eluf-Neto, J. Coronary heart disease mortality, cardiovascular disease mortality and all-cause mortality attributable to dietary intake over 20years in Brazil. Int J Cardiol. 2016. 217:64-8. doi:10.1016/j.ijcard.2016.04.176. | Intervention/Exposure
148 | Roberge, JB, Van Hulst, A, Barnett, TA, Drapeau, V, Benedetti, A, Tremblay, A, Henderson, M. Lifestyle Habits, Dietary Factors, and the Metabolically Unhealthy Obese Phenotype in Youth. Journal of Pediatrics. 2019. 204:46-52.e1. doi:10.1016/j.jpeds.2018.08.063. | Outcome
149 | Rodriguez-Cano, A, Mier-Cabrera, J, Balas-Nakash, M, Munoz-Manrique, C, Legorreta-Legorreta, J, Perichart-Perera, O. Dietary changes associated with improvement of metabolic syndrome components in postmenopausal women receiving two different nutrition interventions. Menopause. 2015. 22:758-64. doi:10.1097/gme.0000000000000400. | Intervention/Exposure; Outcome
150 | Rompay, MIV, McKeown, NM, Goodman, E, Eliasziw, M, Chomitz, VR, Gordon, CM, Economos, CD, Sacheck, JM. Sugar-Sweetened Beverage Intake Is Positively Associated with Baseline Triglyceride Concentrations, and Changes in Intake Are Inversely Associated with Changes in HDL Cholesterol over 12 Months in a Multi-Ethnic Sample of Children1-3. Journal of Nutrition. 2015. 145:2389-2395. doi:10.3945/jn.115.212662. | Sample size
151 | Ross, SM. Cardiovascular disease mortality: the deleterious effects of excess dietary sugar intake. Holist Nurs Pract. 2015. 29:53-7. doi:10.1097/hnp.0000000000000066. | Study design; Publication status
152 | Ryman, TK, Boyer, BB, Hopkins, S, Philip, J, Beresford, SA, Thompson, B, Heagerty, PJ, Pomeroy, JJ, Thummel, KE, Austin, MA. Associations between diet and cardiometabolic risk among Yup’ik Alaska Native people using food frequency questionnaire dietary patterns. Nutr Metab Cardiovasc Dis. 2015. 25:1140-5. doi:10.1016/j.numecd.2015.08.003. | Study design; Intervention/Exposure
153 | Sakurai, K, Fujiwara, N, Takahashi, K, Nakayashiro, M. Excessive soft drink may induce pulmonary hypertension via thiamine deficiency. Pediatr Int. 2019. 61:823-824. doi:10.1111/ped.13913. | Study design; Intervention/Exposure
154 | Sanjeevi, N, Lipsky, LM, Nansel, TR. Cardiovascular Biomarkers in Association with Dietary Intake in a Longitudinal Study of Youth with Type 1 Diabetes. Nutrients. 2018. 10. doi:10.3390/nu10101552. | Health status
155 | Santiago, S, Zazpe, I, Gea, A, de la Rosa, PA, Ruiz-Canela, M, Martinez-Gonzalez, MA. Healthy-eating attitudes and the incidence of cardiovascular disease: the SUN cohort. Int J Food Sci Nutr. 2017. 68:595-604. doi:10.1080/09637486.2016.1265100. | Intervention/Exposure
156 | Saritas, A, Dikici, S, Gunes, H. Adverse effects of energy drinks. The American journal of emergency medicine. 2015. 33:461-462. doi:10.1016/j.ajem.2014.11.054. | Intervention/Exposure; Publication status
157 | Sayon-Orea, C, Martinez-Gonzalez, MA, Gea, A, Alonso, A, Pimenta, AM, Bes-Rastrollo, M. Baseline consumption and changes in sugar-sweetened beverage consumption and the incidence of hypertension: The SUN project. Clin Nutr. 2015. 34:1133-40. doi:10.1016/j.clnu.2014.11.010. | Study design; Outcome
158 | Schumacher, TL, Burrows, TL, Cliff, DP, Jones, RA, Okely, AD, Baur, LA, Morgan, PJ, Callister, R, Boggess, MM, Collins, CE. Dietary Intake Is Related to Multifactor Cardiovascular Risk Score in Obese Boys. Healthcare (Basel). 2014. 2:282-98. doi:10.3390/healthcare2030282. | Outcome
159 | Schwarz, JM, Noworolski, SM, Erkin-Cakmak, A, Korn, NJ, Wen, MJ, Tai, VW, Jones, GM, Palii, SP, Velasco-Alin, M, Pan, K, Patterson, BW, Gugliucci, A, Lustig, RH, Mulligan, K. Effects of Dietary Fructose Restriction on Liver Fat, De Novo Lipogenesis, and Insulin Kinetics in Children With Obesity. Gastroenterology. 2017. 153:743-752. doi:10.1053/j.gastro.2017.05.043. | Intervention/Exposure; Outcome; Study duration
160 | Schwingshackl, L, Knüppel, S, Michels, N, Schwedhelm, C, Hoffmann, G, Iqbal, K, De Henauw, S, Boeing, H, Devleesschauwer, B. Intake of 12 food groups and disability-adjusted life years from coronary heart disease, stroke, type 2 diabetes, and colorectal cancer in 16 European countries. European Journal of Epidemiology. 2019. 34:765-775. doi:10.1007/s10654-019-00523-4. | Intervention/Exposure; Outcome
161 | Seferidi, P, Millett, C, Laverty, AA. Sweetened beverage intake in association to energy and sugar consumption and cardiometabolic markers in children. Pediatr Obes. 2018. 13:195-203. doi:10.1111/ijpo.12194. | Study design
162 | Setayeshgar, S, Ekwaru, JP, Maximova, K, Majumdar, SR, Storey, KE, McGavock, J, Veugelers, PJ. Dietary intake and prospective changes in cardiometabolic risk factors in children and youth. Appl Physiol Nutr Metab. 2017. 42:39-45. doi:10.1139/apnm-2016-0215. | Sample size
163 | Setayeshgar, S, Whiting, SJ, Pahwa, P, Vatanparast, H. Predicted 10-year risk of cardiovascular disease among Canadian adults using modified Framingham Risk Score in association with dietary intake. Appl Physiol Nutr Metab. 2015. 40:1068-74. doi:10.1139/apnm-2015-0074. | Study design
164 | Shams, N, Niaz, F, Motwani, R, Shaikh, Z, Saleem, F. Obesity and hypertension in female medical students; frequency and risk factors. Journal of the Liaquat University of Medical and Health Sciences. 2015. 14:26-32. | Study design; Intervention/Exposure
165 | Sharafi, M, Duffy, VB, Miller, RJ, Winchester, SB, Huedo-Medina, TB, Sullivan, MC. Dietary behaviors of adults born prematurely may explain future risk for cardiovascular disease. Appetite. 2016. 99:157-167. doi:10.1016/j.appet.2016.01.007. | Study design; Intervention/Exposure; Outcome
166 | Shehab, A, Elkilany, GEN, Singh, RB, Hristova, K, Chaves, H, Cornélissen, G, Otsuka, K. Coronary risk factors in South West Asia. World Heart Journal. 2015. 7:21-29. | Study design; Other; Not primary research (review)
167 | Shi, Z, Ruel, G, Dal Grande, E, Pilkington, R, Taylor, AW. Soft drink consumption and multimorbidity among adults. Clin Nutr ESPEN. 2015. 10:e71-e76. doi:10.1016/j.clnesp.2015.01.001. | Study design
168 | Shikany, JM, Judd, SE, Letter, AJ, Ard, JD, Newby, PK. Dietary contributors to glycemic load in the REasons for Geographic and Racial Differences in Stroke study. Nutrition. 2015. 31:708-15. doi:10.1016/j.nut.2014.11.017. | Intervention/Exposure; Outcome
169 | Shikany, JM, Safford, MM, Bryan, J, Newby, PK, Richman, JS, Durant, RW, Brown, TM, Judd, SE. Dietary Patterns and Mediterranean Diet Score and Hazard of Recurrent Coronary Heart Disease Events and All-Cause Mortality in the REGARDS Study. J Am Heart Assoc. 2018. 7. doi:10.1161/jaha.117.008078. | Intervention/Exposure
170 | Shikany, JM, Safford, MM, Newby, PK, Durant, RW, Brown, TM, Judd, SE. Southern Dietary Pattern is Associated With Hazard of Acute Coronary Heart Disease in the Reasons for Geographic and Racial Differences in Stroke (REGARDS) Study. Circulation. 2015. 132:804-14. doi:10.1161/circulationaha.114.014421. | Intervention/Exposure
171 | Shim, JS, Kang, NH, Lee, JS, Kim, KN, Chung, HK, Chung, HR, Kim, HJ, Ahn, YS, Chang, MJ. Socioeconomic burden of sugar-sweetened beverages consumption in Korea. Nutr Res Pract. 2019. 13:134-140. doi:10.4162/nrp.2019.13.2.134. | Study design; Outcome
172 | Shin, Y, Lee, S, Kim, Y. Sweet Preference Associated with the Risk of Hypercholesterolemia Among Middle-Aged Women in Korea. J Atheroscler Thromb. 2018. 25:1215-1221. doi:10.5551/jat.43000. | Intervention/Exposure
173 | Siervo, M, Montagnese, C, Mathers, JC, Soroka, KR, Stephan, BC, Wells, JC. Sugar consumption and global prevalence of obesity and hypertension: an ecological analysis. Public Health Nutr. 2014. 17:587-96. doi:10.1017/s1368980013000141. | Study design
174 | Simpson, EJ, Mendis, B, Macdonald, IA. Orange juice consumption and its effect on blood lipid profile and indices of the metabolic syndrome; a randomised, controlled trial in an at-risk population. Food Funct. 2016. 7:1884-91. doi:10.1039/c6fo00039h. | Intervention/Exposure
175 | Sonestedt, E, Hellstrand, S, Drake, I, Schulz, CA, Ericson, U, Hlebowicz, J, Persson, MM, Gullberg, B, Hedblad, B, Engstrom, G, Orho-Melander, M. Diet Quality and Change in Blood Lipids during 16 Years of Follow-up and Their Interaction with Genetic Risk for Dyslipidemia. Nutrients. 2016. 8. doi:10.3390/nu8050274. | Study design; Intervention/Exposure; Outcome
176 | Soto, R, Guilloty, N, Anzalota, L, Rosario, Z, Cordero, JF, Palacios, C. Association between maternal diet factors and hemoglobin levels, glucose tolerance, blood pressure and gestational age in a Hispanic population. Arch Latinoam Nutr. 2015. 65:86-96. | Study design; Intervention/Exposure; Outcome
177 | Sotos-Prieto, M, Mattei, J, Cook, NR, Hu, FB, Willett, WC, Chiuve, SE, Rimm, EB, Sesso, HD. Association Between a 20-Year Cardiovascular Disease Risk Score Based on Modifiable Lifestyles and Total and Cause-Specific Mortality Among US Men and Women. J Am Heart Assoc. 2018. 7:e010052. doi:10.1161/jaha.118.010052. | Intervention/Exposure
178 | Srour, B, Fezeu, LK, Kesse-Guyot, E, Alles, B, Mejean, C, Andrianasolo, RM, Chazelas, E, Deschasaux, M, Hercberg, S, Galan, P, Monteiro, CA, Julia, C, Touvier, M. Ultra-processed food intake and risk of cardiovascular disease: prospective cohort study (NutriNet-Sante). Bmj. 2019. 365:l1451. doi:10.1136/bmj.l1451. | Intervention/Exposure
179 | Srour, B, Fezeu, LK, Kesse-Guyot, E, Allès, B, Méjean, C, Andrianasolo, RM, Chazelas, E, Deschasaux, M, Hercberg, S, Galan, P, Monteiro, CA, Julia, C, Touvier, M. Ultra-processed food intake and risk of cardiovascular disease: Prospective cohort study (NutriNet-Santé). BMJ (Online). 2019. 365. doi:10.1136/bmj.l1451. | Intervention/Exposure
180 | Stańczyk, M, Tomczyk, D, Grzelak, M, Topolska-Kusiak, J, Raczyński, P, Tkaczyk, M. Metabolic profile and dietary fructose intake in prehypertensive and hypertensive adolescents. Pediatria i Medycyna Rodzinna. 2016. 12:428-435. doi:10.15557/PiMR.2016.0043. | Study design; Intervention/Exposure
181 | Stanhope, KL, Medici, V, Bremer, AA, Lee, V, Lam, HD, Nunez, MV, Chen, GX, Keim, NL, Havel, PJ. A dose-response study of consuming high-fructose corn syrup-sweetened beverages on lipid/lipoprotein risk factors for cardiovascular disease in young adults. Am J Clin Nutr. 2015. 101:1144-54. doi:10.3945/ajcn.114.100461. | Study duration
182 | Stewart, RA, Wallentin, L, Benatar, J, Danchin, N, Hagstrom, E, Held, C, Husted, S, Lonn, E, Stebbins, A, Chiswell, K, Vedin, O, Watson, D, White, HD. Dietary patterns and the risk of major adverse cardiovascular events in a global study of high-risk patients with stable coronary heart disease. Eur Heart J. 2016. 37:1993-2001. doi:10.1093/eurheartj/ehw125. | Intervention/Exposure
183 | Streppel, MT, Sluik, D, van Yperen, JF, Geelen, A, Hofman, A, Franco, OH, Witteman, JC, Feskens, EJ. Nutrient-rich foods, cardiovascular diseases and all-cause mortality: the Rotterdam study. Eur J Clin Nutr. 2014. 68:741-7. doi:10.1038/ejcn.2014.35. | Intervention/Exposure
184 | Svendsen, K, Henriksen, HB, Ostengen, B, Jacobs, DR, Jr, Telle-Hansen, VH, Carlsen, MH, Retterstol, K. Evaluation of a short Food Frequency Questionnaire to assess cardiovascular disease-related diet and lifestyle factors. Food Nutr Res. 2018. 62. doi:10.29219/fnr.v62.1370. | Study design; Intervention/Exposure; Outcome
185 | Tasevska, N, Park, Y, Jiao, L, Hollenbeck, A, Subar, AF, Potischman, N. Sugars and risk of mortality in the NIH-AARP Diet and Health Study. Am J Clin Nutr. 2014. 99:1077-88. doi:10.3945/ajcn.113.069369. | Date
186 | Tasevska, N, Pettinger, M, Kipnis, V, Midthune, D, Tinker, LF, Potischman, N, Neuhouser, ML, Beasley, JM, Van Horn, L, Howard, BV, Liu, S, Manson, JE, Shikany, JM, Thomson, CA, Prentice, RL. Associations of Biomarker-Calibrated Intake of Total Sugars With the Risk of Type 2 Diabetes and Cardiovascular Disease in the Women’s Health Initiative Observational Study. Am J Epidemiol. 2018. 187:2126-2135. doi:10.1093/aje/kwy115. | Intervention/Exposure
187 | Taskinen, MR, Soderlund, S, Bogl, LH, Hakkarainen, A, Matikainen, N, Pietilainen, KH, Rasanen, S, Lundbom, N, Bjornson, E, Eliasson, B, Mancina, RM, Romeo, S, Almeras, N, Pepa, GD, Vetrani, C, Prinster, A, Annuzzi, G, Rivellese, A, Despres, JP, Boren, J. Adverse effects of fructose on cardiometabolic risk factors and hepatic lipid metabolism in subjects with abdominal obesity. J Intern Med. 2017. 282:187-201. doi:10.1111/joim.12632. | Study design; Intervention/Exposure
188 | Telford, RD, Cunningham, RB, Waring, P, Telford, RM, Potter, JM, Hickman, PE, Abhayaratna, WP. Sensitivity of blood lipids to changes in adiposity, exercise, and diet in children. Med Sci Sports Exerc. 2015. 47:974-82. doi:10.1249/mss.0000000000000493. | Intervention/Exposure
189 | Thornley, S, Marshall, RJ, Bach, K, Koopu, P, Reynolds, G, Sundborn, G, Ei, WL. Sugar, dental caries and the incidence of acute rheumatic fever: a cohort study of Maori and Pacific children. J Epidemiol Community Health. 2017. 71:364-370. doi:10.1136/jech-2016-208219. | Intervention/Exposure; Outcome
190 | Ulven, SM, Leder, L, Elind, E, Ottestad, I, Christensen, JJ, Telle-Hansen, VH, Skjetne, AJ, Raael, E, Sheikh, NA, Holck, M, Torvik, K, Lamglait, A, Thyholt, K, Byfuglien, MG, Granlund, L, Andersen, LF, Holven, KB. Exchanging a few commercial, regularly consumed food items with improved fat quality reduces total cholesterol and LDL-cholesterol: a double-blind, randomised controlled trial. Br J Nutr. 2016. 116:1383-1393. doi:10.1017/s0007114516003445. | INCLUDE: CVD (2y and older); Intervention/Exposure
191 | Umpleby, M, Shojaee-Moradie, F, Fielding, B, Li, X, Isherwood, C, Jackson, N, Wilinska, G, Hovorka, R, Bell, J, Thomas, EL, etal, . A diet low in sugar reduces the production of atherogenic lipoproteins in men with high liver fat. Atherosclerosis.. 2015. 241:e46. | Publication status
192 | Varsamis, P, Formosa, MF, Larsen, RN, Reddy-Luthmoodoo, M, Jennings, GL, Cohen, ND, Grace, M, Hawley, JA, Devlin, BL, Owen, N, etal, . Between-meal sucrose-sweetened beverage consumption impairs glycaemia and lipid metabolism during prolonged sitting: a randomized controlled trial. Clinical nutrition (edinburgh, scotland). 2018. doi:10.1016/j.clnu.2018.08.021. | Outcome; Study duration
193 | Viester, L, Verhagen, Ealm, Bongers, PM, van der Beek, AJ. Effectiveness of a Worksite Intervention for Male Construction Workers on Dietary and Physical Activity Behaviors, Body Mass Index, and Health Outcomes: Results of a Randomized Controlled Trial. Am J Health Promot. 2018. 32:795-805. doi:10.1177/0890117117694450. | Intervention/Exposure; Outcome
194 | Vitale, M, Masulli, M, Cocozza, S, Anichini, R, Babini, AC, Boemi, M, Bonora, E, Buzzetti, R, Carpinteri, R, Caselli, C, Ceccarelli, E, Cignarelli, M, Citro, G, Clemente, G, Consoli, A, Corsi, L, De Gregorio, A, Di Bartolo, P, Di Cianni, G, Fontana, L, Garofolo, M, Giorda, CB, Giordano, C, Grioni, S, Iovine, C, Longhitano, S, Mancastroppa, G, Mazzucchelli, C, Montani, V, Mori, M, Perriello, G, Rinaldi, ME, Ruffo, MC, Salvi, L, Sartore, G, Scaranna, C, Tonutti, L, Zamboni, C, Zogheri, A, Krogh, V, Cappellini, F, Signorini, S, Riccardi, G, Vaccaro, O. Sex differences in food choices, adherence to dietary recommendations and plasma lipid profile in type 2 diabetes - The TOSCA.IT study. Nutr Metab Cardiovasc Dis. 2016. 26:879-85. doi:10.1016/j.numecd.2016.04.006. | Health status
195 | Voortman, T, Kiefte-de Jong, JC, Ikram, MA, Stricker, BH, van Rooij, FJA, Lahousse, L, Tiemeier, H, Brusselle, GG, Franco, OH, Schoufour, JD. Adherence to the 2015 Dutch dietary guidelines and risk of non-communicable diseases and mortality in the Rotterdam Study. Eur J Epidemiol. 2017. 32:993-1005. doi:10.1007/s10654-017-0295-2. | Intervention/Exposure
196 | Vorster, HH, Kruger, A, Wentzel-Viljoen, E, Kruger, HS, Margetts, BM. Added sugar intake in South Africa: findings from the Adult Prospective Urban and Rural Epidemiology cohort study. Am J Clin Nutr. 2014. 99:1479-86. doi:10.3945/ajcn.113.069005. | Outcome; Country
197 | Vyas, A, Rubenstein, L, Robinson, J, Seguin, RA, Vitolins, MZ, Kazlauskaite, R, Shikany, JM, Johnson, KC, Snetselaar, L, Wallace, R. Diet drink consumption and the risk of cardiovascular events: a report from the Women’s Health Initiative. J Gen Intern Med. 2015. 30:462-8. doi:10.1007/s11606-014-3098-0. | Intervention/Exposure
198 | Warfa, K, Drake, I, Wallström, P, Engström, G, Sonestedt, E. Association between sucrose intake and acute coronary event risk and effect modification by lifestyle factors: Malmö Diet and Cancer Cohort Study. British Journal of Nutrition. 2016. 116:1611-1620. doi:10.1017/S0007114516003561. | Other; Duplicate of Ref 8852
199 | Whitfield, P, Parry-Strong, A, Walsh, E, Weatherall, M, Krebs, JD. The effect of a cinnamon-, chromium- and magnesium-formulated honey on glycaemic control, weight loss and lipid parameters in type 2 diabetes: an open-label cross-over randomised controlled trial. Eur J Nutr. 2016. 55:1123-31. doi:10.1007/s00394-015-0926-x. | Intervention/Exposure; Health status
200 | Williams, EJ, Baines, KJ, Berthon, BS, Wood, LG. Effects of an Encapsulated Fruit and Vegetable Juice Concentrate on Obesity-Induced Systemic Inflammation: A Randomised Controlled Trial. Nutrients. 2017. 9. doi:10.3390/nu9020116. | Intervention/Exposure
201 | Winkvist, A, Klingberg, S, Nilsson, LM, Wennberg, M, Renstrom, F, Hallmans, G, Boman, K, Johansson, I. Longitudinal 10-year changes in dietary intake and associations with cardio-metabolic risk factors in the Northern Sweden Health and Disease Study. Nutr J. 2017. 16:20. doi:10.1186/s12937-017-0241-x. | Study design; Outcome
202 | Xu, X, Byles, J, Shi, Z, McElduff, P, Hall, J. Dietary pattern transitions, and the associations with BMI, waist circumference, weight and hypertension in a 7-year follow-up among the older Chinese population: a longitudinal study. BMC Public Health. 2016. 16:743. doi:10.1186/s12889-016-3425-y. | Intervention/Exposure
203 | Yang, H, Kim, H, Kim, JM, Chung, HW, Chang, N. Associations of dietary intake and metabolic syndrome risk parameters in Vietnamese female marriage immigrants in South Korea: The KoGES follow-up study. Nutr Res Pract. 2016. 10:313-20. doi:10.4162/nrp.2016.10.3.313. | Study design; Intervention/Exposure; Outcome
204 | Yang, Q, Zhang, Z, Gregg, EW, Flanders, WD, Merritt, R, Hu, FB. Added sugar intake and cardiovascular diseases mortality among US adults. JAMA Intern Med. 2014. 174:516-24. doi:10.1001/jamainternmed.2013.13563. | Date
205 | Yau, AM, McLaughlin, J, Gilmore, W, Maughan, RJ, Evans, GH. The Acute Effects of Simple Sugar Ingestion on Appetite, Gut-Derived Hormone Response, and Metabolic Markers in Men. Nutrients. 2017. 9. doi:10.3390/nu9020135. | Outcome; Study duration
206 | Zheng, Y, Li, Y, Huang, T, Cheng, HL, Campos, H, Qi, L. Sugar-sweetened beverage intake, chromosome 9p21 variants, and risk of myocardial infarction in Hispanics. Am J Clin Nutr. 2016. 103:1179-84. doi:10.3945/ajcn.115.107177. | Study design; Outcome
207 | Zhou, L, Feng, Y, Yang, Y, Zhao, X, Fan, Y, Rong, J, Liu, D, Zhao, L, Yu, Y. Diet behaviours and hypertension in US adults: the National Health and Nutrition Examination Survey 2013-2014. J Hypertens. 2019. 37:1230-1238. doi:10.1097/hjh.0000000000002037. | Study design; Intervention/Exposure
208 | Zoellner, J, Connell, C, Madson, MB, Thomson, JL, Landry, AS, Fontenot Molaison, E, Blakely Reed, V, Yadrick, K. HUB city steps: a 6-month lifestyle intervention improves blood pressure among a primarily African-American community. J Acad Nutr Diet. 2014. 114:603-12. doi:10.1016/j.jand.2013.11.020. | Intervention/Exposure

xi Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xii The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead ( The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups ).