# WHAT IS THE RELATIONSHIP BETWEEN ADDED SUGARS CONSUMPTION AND RISK OF CARDIOVASCULAR DISEASE?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between added sugars consumption and risk of cardiovascular disease?

### What is the answer to the question?

- Limited evidence from prospective cohort studies that were based primarily on sugar-sweetened beverages suggests that higher consumption of added sugars in adulthood is associated with increased risk of cardiovascular disease mortality.
- Insufficient evidence is available to determine the relationship between added sugars consumption and risk of cardiovascular disease in children.
- Insufficient evidence is available to determine the relationship between added sugars intake in adulthood and cardiovascular disease risk profile.
- Insufficient evidence is available to determine the relationship between added sugars intake in adulthood and risk of stroke.
- Insufficient evidence is available to determine the relationship between added sugars intake in adulthood and incident ischemic cardiovascular disease events.
- Insufficient evidence is available to determine the relationship between added sugars intake in adulthood and risk of peripheral artery disease.
- Insufficient evidence is available to determine the relationship between added sugars intake in adulthood and risk of heart failure.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Beverages and Added Sugars Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.

### What is the population of interest?

- The population of interest for the intervention/exposure was all ages (birth through older adulthood).
- The population of interest for the intermediate outcomes was all ages 2 years and older for controlled trials and ages 2-18 years for observational studies.
- The population of interest for the endpoint health outcomes was all ages 2 years and older.

### What evidence was found?

- This review includes 23 studies: 3 in children, 20 in adults
- The exposure or intervention of interest was added sugars. This included total added sugars and added sugars from single, substantial sources like sugar-sweetened beverages (SSB).
- Evidence in children:
  ○ All 3 studies examined intermediate outcomes, primarily lipid profiles. Two found greater added sugars intake related to worse lipid profiles in children. The third found no relationship.
  ○ Evidence was limited by the small number of studies, wide variability in participant age, and inconsistency in outcomes measured.
- Evidence in adults:
  ○ Four of the 6 articles reporting intermediate outcome data found no relationship with added sugars. The remaining 2 found added sugars related to both total cholesterol and triglyceride levels.
  ○ Cardiovascular disease-related mortality risk was positively related to greater added sugars intake when the exposure was measured multiple times.
  ○ No conclusions could be drawn for peripheral artery disease, stroke, or heart failure.
  ○ Evidence was limited by poor adjustment for confounders, use of different exposures and outcomes, and measuring the exposure only once.

### How up-to-date is this systematic review?

- This review searched for studies from September 2014 to September 2019.

## FULL REVIEW

### Systematic review question

What is the relationship between added sugars consumption and risk of cardiovascular disease?

### Conclusion statements and grades

Limited evidence from prospective cohort studies that were based primarily on sugar-sweetened beverages suggests that higher consumption of added sugars in adulthood is associated with increased risk of cardiovascular disease mortality. (Grade: Limited)

Insufficient evidence is available to determine the relationship between added sugars consumption and risk of cardiovascular disease in children. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between added sugars intake in adulthood and cardiovascular disease risk profile. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between added sugars intake in adulthood and risk of stroke. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between added sugars intake in adulthood and incident ischemic cardiovascular disease events. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between added sugars intake in adulthood and risk of peripheral artery disease. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between added sugars intake in adulthood and risk of heart failure. (Grade: Grade not assignable)

### Summary of the evidence

- 23 studies examined the relationship between added sugars consumption and the risk of cardiovascular disease (CVD)^1–23^:
  ○ Children: 3 studies, including 1 randomized controlled trial (RCT) and 2 prospective cohort studies (PCSs)
  ○ Adults: 20 studies, including 4 RCTs, 2 crossover studies, and 14 PCSs
- The added sugars intervention/exposure included:
  ○ Total added sugars intake from foods and beverages
  ○ Added sugars from a single substantial source of overall added sugars intake (e.g., sugar-sweetened beverages [SSB], total sucrose intake)
- CVD outcomes considered:
  ○ Intermediate outcomes: Total cholesterol, LDL-C, HDL-C, triglycerides, and blood pressure (systolic and diastolic)
    ■ Children: included intermediate outcome data from RCTs and observational studies
    ■ Adults: included intermediate outcome data from RCTs and crossover studies only
  ○ Endpoint outcomes: CVD (including myocardial infarction, coronary heart disease, and coronary artery disease; congestive heart failure; and peripheral artery disease), stroke (separating ischemic and hemorrhagic when possible), venous thrombosis, and CVD-related mortality
    ■ Children and adults: included endpoint outcome data from RCTs, crossover, and observational studies
- Evidence in children:
  ○ Three studies reported on intermediate CVD outcomes in children; no studies looking at endpoint outcomes in children met the inclusion criteria.
  ○ Findings from the 1 RCT and 1 cohort study found greater added sugars intake related to worse lipid profiles in children, namely detrimental change in total cholesterol and HDL-C over time.
  ○ The third study did not find a significant relationship between added sugars consumption and CVD outcomes.
  ○ The body of evidence was limited substantially by the small number of studies, the variability in age of the participants, and inconsistency in outcomes measured.
- Evidence in adults:
  ○ Intermediate outcomes:
    ■ Three RCTs reported in 4 articles and 2 crossover studies examined intermediate CVD outcomes; 4 of these studies found no significant effect of added sugars consumption.
    ■ One RCT found that reducing added sugars consumption led to improved triglyceride levels, and the second paper from a larger sample of participants from the same RCT found that continued high levels of SSB consumption led to detrimental changes in total cholesterol and triglyceride levels.
    ■ RCT evidence was limited by small sample sizes and inconsistency in exposures and outcomes measured.
  ○ Endpoint outcomes:
    ■ CVD-related mortality was assessed by 8 PCSs; 6 of the 8 found no significant relationship; 1 found a relationship before adjustment for adiposity, and the other reported repeat exposure assessment in 2 independent cohorts and found a significant, positive association.
    ■ A small number of studies examined ischemic CVD events, peripheral artery disease, stroke, and heart failure, which limited the ability to draw conclusions.
    ■ Most studies adjusted for adiposity, though four studies presented data both with and without adjustment, and all but one found the relationship did not change.
    ■ Observational evidence was limited by inadequate adjustment for confounders, inconsistency in exposures and outcomes measured, and measures of exposure taken at baseline only.

### Description of the evidence

This systematic review examining the relationship between added sugars consumption and risk of CVD included 23 articles published between September 2014 and September 2019. Three studies were conducted in children and 20 in adults.

Study designs:

- Children: 3 articles
  ○ RCTs: 1 article^4^
  ○ Prospective cohort studies: 2 articles^8,9^
- Adults: 20 articles
  ○ Parallel-arm RCTs: 4 articles^2,5,6,11^
  ○ Crossover RCTs: 2 articles^13,22^
  ○ Prospective cohort studies: 14 articles^1,3,7,10,12,14–21,23^

In children, the RCT was conducted in Brazil,^4^ one prospective cohort study was conducted in the United States,^8^ and the other in the Netherlands.^9^

The studies in adults were conducted in the following countries: six studies in the United States^1,3,12,17,18,20^; four in Sweden^7,19,21,23^; two each in Denmark,^2,5^ Mexico,^6,11^ and the United Kingdom^13,22^; one each in Hong Kong,^10^ Japan,^15^ and Singapore^16^; and one multi-country European cohort.^14^

#### Population

Studies were included if the participants were generally healthy or at risk for chronic disease.

The three studies in children enrolled a range of ages, with the RCT studying 478, 11-year-old children and following them for one school year^4^; one prospective cohort study studying 2,223, 9-10-year-old children with a 10-year follow up^8^; and the other studying 1,390 children approximately 13-months old and following them through age 6.^9^ Two of the samples were racially diverse with 59% ‘non-white skin’ participants in the RCT^4^ and 51% Black in the US cohort,^8^ while the third study, conducted in the Netherlands, did not report race/ethnicity data.^9^

The four RCTs and two crossover studies conducted in adults enrolled a broad range of ages, primarily middle-aged adults, with one focusing specifically on older men^22^ and another exclusively enrolling women.^6^ The sample sizes ranged from 27 to 268. Only one study reported race/ethnicity data, and the sample was 80% white.^13^ The prospective cohort studies were similar, enrolling large cohorts of predominantly white, middle-aged adults. Sample sizes ranged from 2,888 to 202,907.

#### Intervention/exposure/comparator

The intervention or exposure of interest for this question was added sugars, which included studies examining total added sugars intake from foods and beverages as well as studies assessing added sugars from a single substantial source of overall added sugars intake (e.g., SSBs or total sucrose intake).

Two of the three studies in children, including the RCT, focused on SSB intake,^4,9^ while one of the prospective cohort studies examined added sugars intake from all foods and beverages.^8^

For adults, two RCTs and one crossover study used total added sugars as the intervention,^11,13,22^ while the remaining studies focused specifically on SSBs.^2,5,6^

The prospective cohort studies also assessed a variety of exposures, with eight examining SSB intake^1,3,12,14,16–19^; three examining total added sugars intake^10,15,20^; and three specifically examining sucrose intake.^7,21,23^

#### Outcomes

The outcomes of interest in children included both intermediate and endpoint outcomes; however, the eligible data only looked at intermediate outcomes. Total cholesterol and HDL cholesterol were assessed in two studies, while SBP, DBP, LDL, and triglycerides were each measured in one study.^9^

In order to focus on the strongest available evidence, included outcomes in adults differed by study design. For experimental designs, intermediate and endpoint outcomes were included; for observational studies, only endpoint CVD outcomes were included. The eligible data were synthesized according to the following categories: CVD risk profile, which included blood pressure, cholesterol, and triglycerides (4 RCTs and 2 crossover studies); CVD-related mortality (8 prospective cohort studies); ischemic CVD event incidence (3 prospective cohort studies); peripheral artery disease incidence (PAD, 2 prospective cohort studies); stroke incidence (1 prospective cohort study); and heart failure incidence (1 prospective cohort study).

### Evidence synthesis

#### Children

The RCT^4^ and one cohort study^8^ examined similarly-aged children and showed greater SSB and total added sugars intake related to worse lipid profiles, though they examined different outcomes, total cholesterol and HDL, respectively. The remaining cohort study examined a broader range of outcomes in younger children and did not find any significant associations (Table 1).^9^

##### Lipid profile

De Moraes et al^4^ used school-based cluster randomization to test a behavioral approach to reduce SSB intake in 4^th^ grade Brazilian children in which the intervention group received water-promoting messaging, education, and supplies (i.e., water bottles). The control group received general health education and consumed their usual diet. The intervention ran for one full school year and resulted in significantly lower total cholesterol and lower incidence of moderately high total cholesterol (≥150 mg/dL) and hypercholesterolemia (≥170 mg/dL) compared to the control group.

Lee et al^8^ assessed added sugar intake from all foods and beverages in girls age 9-10 years-old at baseline and then annually for 10-years of follow-up. Consuming ≥10% of total energy from added sugars was associated with an annual decrease in HDL. Over the 10-year follow up, consuming less than 10% total energy as added sugars was associated with higher HDL.

Leermakers et al^9^ examined consumption of sugar-containing beverages in 13-month-old toddlers and outcomes at 6 years of age. Intake of sugar-containing beverages at baseline was not associated with the outcomes examined five years later, including systolic and diastolic blood pressure, total cholesterol, HDL, LDL, and triglycerides.

These findings were limited by the small number of studies, and the individual studies were impacted by inconsistency in population ages, exposures, and outcome assessed; inadequate adjustment for confounders; inconsistent findings with limited directness to the outcome of interest; and poor generalizability (see Table 2 and Table 3). Due to these limitations, the evidence was insufficient to draw a conclusion to the systematic review question.

#### Adults

##### CVD-related mortality

Three large prospective cohort studies examined total added sugars intake and CVD-related mortality.^10,15,20^ Findings were mixed; two found no significant association with CVD-related mortality,^15,20^ while one found greater added sugars intake was related to lower risk but only before adjustment for adiposity.^10^ All other studies on this outcome adjusted for adiposity in all analyses (Table 4).

Five additional prospective cohort studies examined the relationship between added sugars in the form of SSBs and CVD-related mortality^1,3,12,14,16^; four of the five found no significant effect.^1,3,14,16^ The fifth study found that greater intake of SSBs was related to higher risk of CVD-related mortality in two large, independent cohorts.^12^

Adjusting for total energy did not explain discrepant findings across the prospective cohort studies. Anthropometry, a likely mediator of this relationship, was adjusted for in all studies and likely attenuated the relationship between added sugars consumption and CVD-related mortality. The study that showed a significant deleterious effect in both men and women measured SSB intake at baseline and multiple times thereafter in two separate cohorts^12^; all other studies assessed intake at baseline only in a single cohort.

##### CVD risk profile

Four RCTs and two crossover studies examined the relationship between added sugars intake and intermediate CVD outcomes.^2,5,6,11,13,22^

Two articles reported results from the same parallel arm RCT.^2,5^ This study randomized participants to a 6-month intervention of either 1 L/day of sucrose-sweetened soft drinks or aspartame-sweetened diet cola. Bruun et al^2^ found that triglyceride levels were significantly lower in the diet cola group at the end of intervention. Engel et al^5^ found total cholesterol and triglyceride levels were significantly higher in the sugar-sweetened soft drink group at the end of the intervention, but that differences in LDL, HDL, SBP, and DBP were not significant. These analyses were limited by small sample sizes.

The remaining parallel-arm RCTs found no significant relationships.^6,11^ A 9-month intervention in women with overweight or obesity promoted decreased SSB consumption compared to an education-only control and found no significant between-group differences in triglycerides, total cholesterol, LDL, HDL, SBP, or DBP.^6^ The fourth parallel-arm RCT compared a 4-week low-fructose + low-sodium diet to a low-sodium diet and found no significant differences in blood pressure, total cholesterol, or triglycerides.^11^

Of the crossover studies, one found no significant differences between consuming a sugar-reduced diet versus a regular diet for eight weeks in SBP, DBP, total cholesterol, LDL, HDL, or triglycerides.^13^ The other crossover trial found no significant differences between consuming high-sugar and low-sugar diets for 12 weeks in triacylglycerol, total cholesterol, LDL, or HDL in a sample of men.^22^

##### Ischemic CVD events

Three prospective cohort studies measured the incidence of ischemic CVD events.^18,21,23^ Sonestedt et al^21^ examined intake of sucrose from all sources at baseline and incidence of ischemic CVD event, defined as coronary events and ischemic stroke, over a 14-year average follow-up. They also considered individual sources of sucrose, assessing the relationship between SSBs, cookies and cakes, and sweets with the outcome, independently. There was no significant association between baseline intake and incident events. Similarly, Pase et al^18^ showed no significant relationship between sugar-sweetened soft drink intake over an average of 8 years and risk of ischemic stroke in the following 10 years.

The third prospective cohort study found total sucrose intake >15% of total energy intake at baseline was related to greater incidence of coronary events over 17 years of follow-up.^23^ Incidence was not significantly different between groups at lower intake levels.^23^

##### Peripheral artery disease (PAD) incidence

Two prospective cohort studies examined incidence of peripheral artery disease.^7,17^ The first measured sucrose intake in middle-aged adults relative to the Swedish dietary guidelines (sucrose intake ≤10% total energy) and found there was no significant difference in risk of PAD between those consuming above and those consuming below the recommended amount.^7^ The second study examined intake of SSBs in middle-aged US adults and found that baseline intake of 2-6 servings per week was related to lower risk relative of PAD compared to those who consumed lower and higher levels, but this was no longer significant after adjustment for baseline diabetes status.^17^

##### Stroke

One study examined the relationship between SSBs and total stroke risk. Pase et al^18^ found that average intake of sugar-sweetened soft drinks over eight years was not related to risk of stroke over the subsequent 10-year period.

##### Heart failure incidence

Only one study examining the association between added sugars intake and incident heart failure was eligible for inclusion.^19^ The authors assessed SSB intake and found that individuals consuming two or more servings per day at baseline had a higher risk of heart failure over a 12-year average follow-up compared to non-consumers.

Across all outcomes, adiposity (or prevalence of obesity) was an important variable to consider when answering this question, particularly since this review aimed to examine the direct link between added sugar consumption and risk of CVD independent of obesity. Over 75 percent of studies in this body of evidence adjusted for adiposity (e.g., BMI, weight), which, as adiposity is a likely mediator, may have affected the observed magnitude of relationship between added sugars and risk of CVD in these studies. One study found the relationship was significant only before adjustment for adiposity,^10^ while three other studies examined the effect of adjustment for adiposity using sensitivity analysis, and results remained the same both with and without adjustment.^18,19,23^

Funding source(s) of each study were extracted and considered during synthesis.

#### Assessment of the evidence: Adults^ii^

The conclusion statement “evidence from prospective cohort studies that were based primarily on SSBs suggests that higher consumption of added sugars in adulthood is associated with increased risk for cardiovascular disease mortality” was assigned a grade of limited. Publication bias is another concern. Insufficient evidence was available to draw conclusion statements related to CVD risk profile, stroke, ischemic CVD events, peripheral artery disease, or heart failure.

As outlined and described below, the body of evidence examining added sugars consumption and risk of cardiovascular disease was assessed for the following elements used when grading the strength of evidence.

Consistency: The study combining two cohorts with repeat exposure assessment showed a significant relationship with CVD-related mortality, while the studies that only examined one exposure time point showed no significant relationship. This remained true regardless of whether the study looked at total added sugars intake or SSBs as the exposure.

Directness: All evidence comes from prospective cohort studies that were not likely designed to answer this specific question; however, the relationships studied are sufficient for answering this research question. More than half of the studies examined SSBs, specifically, while the others assessed total added sugars intake.

Precision: Most cohorts were large in size, with only one study enrolling fewer than 5,000 participants, and findings were consistent across sample sizes.

Generalizability: The majority of studies enrolled middle-aged adults that were primarily white, suggesting good generalizability for that population, but less generalizability for younger, older, and non-white adults.

Risk of bias: Multiple areas of potential risk of bias impacted these studies, primarily inadequate adjustment for confounders, exposure measurement at baseline only, and failure to account for missing data. (see Table 5 and Table 6)

### Research recommendations

- Distinguish between food and beverage sources of added sugars when conducting intervention or assessing exposure
- Measure added sugars consumption with more accuracy, including use of validated measures and repeat assessment of intake across time
- Consider the important role of obesity and adiposity measures when examining this relationship, including consideration both with and without statistical adjustment for these measures

### Included articles

1 Barrington WE, White E. Mortality outcomes associated with intake of fast-food items and sugar-sweetened drinks among older adults in the Vitamins and Lifestyle (VITAL) study. Public Health Nutr. 2016;19(18):3319–3326. doi: 10.1017/s1368980016001518.27338763
2 Bruun JM, Maersk M, Belza A, Astrup A, Richelsen B. Consumption of sucrose-sweetened soft drinks increases plasma levels of uric acid in overweight and obese subjects: a 6-month randomised controlled trial. Eur J Clin Nutr. 2015;69(8):949–953. doi: 10.1038/ejcn.2015.95.26081486
3 Collin LJ, Judd S, Safford M, Vaccarino V, Welsh JA. Association of sugary beverage consumption with mortality risk in us adults: a secondary analysis of data from the REGARDS Study. JAMA Netw Open. 2019;2(5):e193121. doi: 10.1001/jamanetworkopen.2019.3121.31099861
4 de Moraes MM, Mediano MFF, de Souza RAG, Moura AS, da Veiga GV, Sichieri R. Discouraging soft drink consumption reduces blood glucose and cholesterol of Brazilian elementary students: secondary analysis of a randomized controlled trial. Prev Med. 2017;100:223–228. doi: 10.1016/j.ypmed.2017.04.035.28457714
5 Engel S, Tholstrup T, Bruun JM, Astrup A, Richelsen B, Raben A. Effect of high milk and sugar-sweetened and non-caloric soft drink intake on insulin sensitivity after 6 months in overweight and obese adults: a randomized controlled trial. Eur J Clin Nutr. 2018;72(3):358–366. doi: 10.1038/s41430-017-0006-9.29235560
6 Hernandez-Cordero S, Barquera S, Rodriguez-Ramirez S, . Substituting water for sugar-sweetened beverages reduces circulating triglycerides and the prevalence of metabolic syndrome in obese but not in overweight Mexican women in a randomized controlled trial. J Nutr. 2014;144(11):1742–1752. doi: 10.3945/jn.114.193490.25332472
7 Kulezic A, Bergwall S, Fatemi S, . Healthy diet and fiber intake are associated with decreased risk of incident symptomatic peripheral artery disease - a prospective cohort study. Vasc Med. 2019;24(6):511–518. doi: 10.1177/1358863x19867393.31431146
8 Lee AK, Binongo JN, Chowdhury R, . Consumption of less than 10% of total energy from added sugars is associated with increasing HDL in females during adolescence: a longitudinal analysis. J Am Heart Assoc. 2014;3(1):e000615. doi: 10.1161/jaha.113.000615.24572253
9 Leermakers ET, Felix JF, Jaddoe VW, Raat H, Franco OH, Kiefte-de Jong JC. Sugar-containing beverage intake at the age of 1 year and cardiometabolic health at the age of 6 years: the Generation R Study. Int J Behav Nutr Phys Act. 2015;12:114. doi: 10.1186/s12966-015-0278-1.26377916
10 Liu ZM, Tse LA, Chan D, Wong C, Wong SYS. Dietary sugar intake was associated with increased body fatness but decreased cardiovascular mortality in Chinese elderly: an 11-year prospective study of Mr and Ms OS of Hong Kong. Int J Obes. 2018;42(4):808–816. doi: 10.1038/ijo.2017.292.
11 Madero M, Rodriguez Castellanos FE, Jalal D, . A pilot study on the impact of a low fructose diet and allopurinol on clinic blood pressure among overweight and prehypertensive subjects: a randomized placebo controlled trial. J Am Soc Hypertens. 2015;9(11):837–844. doi: 10.1016/j.jash.2015.07.008.26329473
12 Malik VS, Li Y, Pan A, . Long-term consumption of sugar-sweetened and artificially sweetened beverages and risk of mortality in US adults. Circulation. 2019;139(18):2113–2125. doi: 10.1161/circulationaha.118.037401.30882235
13 Markey O, Le Jeune J, Lovegrove JA. Energy compensation following consumption of sugar-reduced products: a randomized controlled trial. Eur J Nutr. 2016;55(6):2137–2149. doi: 10.1007/s00394-015-1028-5.26349919
14 Mullee A, Romaguera D, Pearson-Stuttard J, . Association between soft drink consumption and mortality in 10 European countries. JAMA Intern Med. 2019. doi: 10.1001/jamainternmed.2019.2478.
15 Nagata C, Wada K, Yamakawa M, . Intake of starch and sugars and total and cause-specific mortality in a Japanese community: the Takayama Study. Br J Nutr. 2019;122(7):820–828. doi: 10.1017/s0007114519001661.32124712
16 Odegaard AO, Koh WP, Yuan JM, Pereira MA. Beverage habits and mortality in Chinese adults. J Nutr. 2015;145(3):595–604. doi: 10.3945/jn.114.200253.25733477
17 Ogilvie RP, Lutsey PL, Heiss G, Folsom AR, Steffen LM. Dietary intake and peripheral arterial disease incidence in middle-aged adults: the Atherosclerosis Risk in Communities (ARIC) Study. Am J Clin Nutr. 2017;105(3):651–659. doi: 10.3945/ajcn.116.137497.28077376
18 Pase MP, Himali JJ, Beiser AS, . Sugar- and artificially sweetened beverages and the risks of incident stroke and dementia: a prospective cohort study. Stroke. 2017;48(5):1139–1146. doi: 10.1161/strokeaha.116.016027.28428346
19 Rahman I, Wolk A, Larsson SC. The relationship between sweetened beverage consumption and risk of heart failure in men. Heart. 2015;101(24):1961–1965. doi: 10.1136/heartjnl-2015-307542.26526418
20 Shah NS, Leonard D, Finley CE, . Dietary patterns and long-term survival: a retrospective study of healthy primary care patients. Am J Med. 2018;131(1):48–55. doi: 10.1016/j.amjmed.2017.08.010.28860032
21 Sonestedt E, Hellstrand S, Schulz CA, . The association between carbohydrate-rich foods and risk of cardiovascular disease is not modified by genetic susceptibility to dyslipidemia as determined by 80 validated variants. PLoS One. 2015;10(4):e0126104. doi: 10.1371/journal.pone.0126104.25898210
22 Umpleby AM, Shojaee-Moradie F, Fielding B, . Impact of liver fat on the differential partitioning of hepatic triacylglycerol into VLDL subclasses on high and low sugar diets. Clin Sci. 2017;131(21):2561–2573. doi: 10.1042/cs20171208.
23 Warfa K, Drake I, Wallstrom P, Engstrom G, Sonestedt E. Association between sucrose intake and acute coronary event risk and effect modification by lifestyle factors: Malmo Diet and Cancer Cohort Study. Br J Nutr. 2016;116(9):1611–1620. doi: 10.1017/s0007114516003561.27774913

Table 1 Evidence in children on added sugars consumption and risk of cardiovascular disease^iii^

Study and Population Characteristics | Intervention/Exposure, Comparator and Outcome(s) | Results | TEI, Confounders, and Study Limitations
de Moraes, 2017 (https://pubmed.ncbi.nlm.nih.gov/28457714-discouraging-soft-drink-consumption-reduces-blood-glucose-and-cholesterol-of-brazilian-elementary-students-secondary-analysis-of-a-randomized-controlled-trial/)^1^*; Cluster RCT, Brazil (secondary analyses using participants who consented to blood draw, 42% of original sample); Baseline N=1140, Analytic N=478 (Attrition: NR); Power: 80% power and a 5% significance level to detect a difference of 0.5 cup in soda consumption between the two groups, with 140 students in each arm of the trial; final sample size with available blood samples of about 480 would be able to detect weight changes and associated changes in metabolic markers; Recruitment: 22 public schools in the metropolitan area of Rio de Janeiro, Brazil; Participant characteristics: fourth-grade children; - Total energy intake: ~2297 kcal/d; - Sex (female): ~44%; - Age: ~10.8y; - Race/ethnicity: 59% Non-white skin; - SES: NR; - Anthropometrics: BMI~18.2 kg/m^2^; 19% Overweight; - Physical activity: NR; - Smoking: NR; Summary of findings:; An 8-month lifestyle intervention to reduce soft drink intake in children resulted in significant reductions in total cholesterol in the intervention group compared to control. | Intervention: Soft drink intake; A healthy lifestyle education program using simple messages encouraging water consumption instead of soft drinks. Education delivered via classroom activities; banners promoting water consumption, and water bottles with the logo of the campaign given to children and school teachers; n=238; Comparator: Control; received two 1hr sessions on general health issues and printed guidelines on healthy eating; n=240; [underlined: Intervention duration]: 7mo of one school year; [underlined: Intervention compliance]: two 24hr dietary recalls and frequency questionnaire on beverage consumption; Study added sugars intake: Soft drinks; - Never to 4 times/mo: 29%; - 2-6 times/wk: 51%; - ≥1 time/d: 16%; Outcome assessment methods/timing:; - Baseline, ~8mo follow-up; - Intermediate outcomes measured: Total cholesterol; - Fasting blood samples collected in schools by trained laboratory technician; serum cholesterol obtained by enzymatic-colorimetric method; - Moderately high total cholesterol defined as ≥150 mg/dL and hypercholesterolemia ≥170 mg/dL | [underlined: Intermediate outcomes:]; [underlined: Total Cholesterol], mg/dL; Within group, change over 1yr:; Control: +2.14; Intervention: −10.34; Between groups:; P<0.001, Effect size=0.06; [underlined: Cholesterol ≥150 mg/dL], % (n); Change within group over time:; Baseline, f/u; Control: 53.2 (125), 56.7 (89); Intervention: 70.7 (159), 55.6 (84); Between groups:; P=0.002; [underlined: Cholesterol ≥170 mg/dL], % (n); Change within group over time:; Baseline, f/u; Control: 26.0 (61), 28.7 (45); Intervention: 39.1 (88), 29.1 (44); Between groups:; P=0.03 | TEI adjusted: Yes; [underlined: TEI], kcal/d; Within group, change over 1yr:; Control: −193.7; Intervention: −384.0; Between groups:; P=0.03, Effect size=0.15; Confounders accounted for:; - Key confounders: sex, age, race/ethnicity, anthropometry; - Other factors considered: total energy intake, protein, fat, food form (beverage); Confounders NOT accounted for:; - Key confounders: SES, physical activity, smoking, naturally occurring sugar intake; - Other factors considered: medications, supplements, sodium, fiber, energy density, family history of CVD; Additional model adjustments: Baseline cholesterol, cluster (class); Limitations:; - Not all key confounders accounted for; - Frequency of participants who consumed soft drinks ≥1/d was higher among ppts with no blood samples compared to those included here who had at least one blood sample; - No analysis plan; Funding source:; Brazilian National Research Institute
Prospective Cohort Studies
Lee, 2014 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC3959678/) ^2^; Prospective Cohort Study, National Heart Lung and Blood Institute’s Growth and Health Study (NGHS), United States; Analytic N=2223; Power: NR; Recruitment: three study sites (Richmond, CA; Cincinnati, OH; Washington, DC); Participant characteristics: adolescent girls (9-10y); - Sex (female): 100%; - Age: 9-10y; - Race/ethnicity: 51% African-American, 49% Caucasian; - SES: Parent education, ≥College graduate 35%; - Anthropometrics: 69% Normal weight, 13% Obese; - Physical activity: score, 32.2; - Smoking: Current (≥7 cigarettes/wk) 0.5%; Summary of findings:; Among adolescent girls, consuming ≥10% of total energy from added sugars was associated in an annual decline in HDL. Over the 10y follow-up, consumption of added sugars <10% total energy was associated with higher HDL. | Exposure of interest: Added sugar intake from all sugar-containing foods and beverages (such as sucrose, fructose, and glucose from soda, desserts, and sweetened grain products); Comparators: categorical; - Low (0 to <10% of total energy); - High (≥10% of total energy); [underlined: Exposure assessment method and timing]:; - 3-d food record (validated); represents dietary intake on both weekdays and weekends; - At baseline, annually for 10y; Outcome assessment methods/timing:; - At visits 1, 3, 5, 7, and 10y; - Intermediate outcomes measured: HDL cholesterol; - Fasting and non-fasting blood samples obtained; non-fasting HDL levels used for analysis | [underlined: Intermediate outcomes:]; [underlined: HDL], by consumption level, mg/dL, β (95% CI); Change per consumption level:; Low (ref); High: −0.26 (0.48 to 0.04), P=0.02; Predicted change over 10yr study period for nonsmoking adolescents of normal weight:; Low: 2.2 (0.09, 4.32), P=0.04; High: −0.4 (−1.32, 0.52), P=0.4; P difference: 0.045; Interaction of added sugars with BMI: P=0.45; Sensitivity analyses assessing impact of assumptions used to calculate amount of added and naturally occurring sugars in foods (e.g., lactose and galactose in dairy products) found no substantial differences in the results. | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, race/ethnicity, physical activity, anthropometry, smoking, naturally occurring sugar intake; - Other factors considered: total energy intake, fiber, fat; Confounders NOT accounted for:; - Key confounders: SES; - Other factors considered: menopausal status, medications, supplements, sodium, protein, energy density, family history of CVD, food form (solid/beverage); Additional model adjustments: Puberty stage, nutrient residuals for other carbohydrates; Limitations:; - Not all key confounders accounted for; - No information on non-completers; - Results not clearly reported; - No preregistered data analysis plan; Funding sources:; NR
Leermakers, 2015 (https://ijbnpa.biomedcentral.com/articles/10.1186/s12966-015-0278-1) ^3^; Prospective Cohort Study, Generation R Study, the Netherlands; Analytic N= 1390-1950; Power: NR; Participant characteristics: toddlers; - Sex (female): 34%; - Age: ~ 13mo; Summary of findings:; There were no significant associations between sugar-containing beverage intake at 12 month and CVD-related outcomes (TC, HDL, LDL, TG, SBP, DBP) at ~6 years old. | Exposure of interest: Sugar-containing beverages (Total SCBs including fruit juices, fruit concentrates, lemonades, soft drinks and sports drinks); 1 svg = 150 mL; Comparators: categorical; sex-specific tertiles; [underlined: Exposure assessment method and timing]:; - Primary caregiver completed FFQ, representing past month; validated; - At baseline (~13mo); Outcome assessment methods/timing:; - At ~5.9yo; - Intermediate outcomes measured: total cholesterol (TC), HDL, LDL, TG, SBP, DBP; - Non-fasting blood samples drawn and TC, HDL, LDL, and TG measured with enzymatic methods; SBP and DBP measured four times using validated automatic sphygmomanometer (average of three measurements used) | [underlined: Systolic Blood Pressure], Linear regression, β (95% CI); Total population (n=1950): NS; Boys: NS; Girls: NS; [underlined: Diastolic Blood Pressure], Linear regression, β (95% CI); Total population (n=1950): NS; Boys: NS; Girls: NS; [underlined: Total Cholesterol], Linear regression, β (95% CI);; Total population: NS; Boys: NS; Girls: NS; [underlined: HDL Cholesterol], Linear regression, β (95% CI);; Total population (n=1390): NS; Boys: NS; Girls: NS; [underlined: LDL Cholesterol], Linear regression, β (95% CI);; Total population: NS; Boys: NS; Girls: NS; [underlined: Triglycerides], Linear regression, β (95% CI); Total population (n=1387): NS; Boys: NS; Girls: NS | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: maternal age, sex, SES (parent), feeding practices (e.g., human milk/infant formula history); - Other factors considered: smoking (maternal), maternal anthropometry; Confounders NOT accounted for:; - Key confounders: gestational age, race/ethnicity, anthropometry at birth or baseline; - Other factors considered: maternal diet, parity, participation in a supplemental food program, family history of CVD, complementary feeding practices; Additional model adjustments: Total energy intake, folic acid supplementation during pregnancy, child diet quality score, hours of watching TV at age 2; Limitations:; - Not all key confounders accounted for; - No information on non-completers; - Exposure data only measured once; - No preregistered data analysis plan; Funding sources:; Erasmus Medical Centre, Rotterdam, the Erasmus University Rotterdam and the Netherlands Organization for Health Research and Development; the Netherlands Organization for Health Research and Development; Nestlé Nutrition (Nestec Ltd.), Metagenics Inc. and AXA

Table 2 Risk of bias for the randomized controlled trial examining added sugars consumption and risk of cardiovascular disease in children^iv,^ ^v^

| Randomization | Identification of participants - randomization | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of the reported result
de Moraes, 2017^1^ | High | Some Concerns | Low | Low | Low | Some Concerns

Table 3 Risk of bias for observational studies examining added sugars consumption and risk of cardiovascular disease in children^vi^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Lee, 2014^2^ | Serious | Low | Low | Low | Low | Low | Serious
Leermakers, 2015^3^ | Serious | Low | Low | Moderate | Moderate | Low | Moderate

Table 4 Evidence in adults on added sugars consumption and risk of cardiovascular disease^vii^

Study and Population Characteristics | Intervention/Exposure, Comparator and Outcome(s) | Results | TEI, Confounders, and Study Limitations
RCTs
Bruun, 2015 (https://pubmed.ncbi.nlm.nih.gov/26081486-consumption-of-sucrose-sweetened-soft-drinks-increases-plasma-levels-of-uric-acid-in-overweight-and-obese-subjects-a-6-month-randomised-controlled-trial/)^4^*; RCT, Denmark; Baseline N=60, Analytic N=47 (Attrition: 22%); Power: NR; Recruitment: two centers at Aarhus University Hospital and Department of Nutrition, Exercise and Sports, Faculty of Science, Copenhagen University; Participant characteristics: adults with overweight and obesity; - Total energy intake: NR; - Sex (female): 72%; - Age: 38.6 (1.1)y (Range 20-50y); - Race/ethnicity: NR; - SES: NR; - Anthropometrics: BMI 32.1 (0.5) kg/m^2^; - Physical activity: ≤10hr/wk (inclusion criteria); - Smoking: 100% nonsmokers; Summary of findings:; In overweight adults and those with obesity, drinking sucrose-sweetened cola (1 L/d) for 6 months significantly increased triglycerides, and triglycerides were significantly higher in the SSSD group than in the groups randomized to consume diet cola (aspartame-sweetened cola, 1 L/d).; * Additional information obtained from primary study: Maersk M, . Am J Clin Nutr 2012; 95: 283–289.22205311 | Intervention: Sucrose-sweetened soft drink (SSSD; Coca Cola; 1 L/d), n=10; Comparator: Aspartame-sweetened diet cola (diet Coca Cola; 1 L/d), n=12; Other interventions: milk, water; [underlined: Intervention duration]: 6mo; [underlined: Intervention compliance]: empty bottles or cartons every 3-4wk; 7-d dietary records at baseline, 3mo, 6mo; compliance NR; Study added sugars intake:; - SSSD at baseline: NR; Outcome assessment methods/timing:; - At baseline, 6mo follow-up; - Intermediate outcomes measured: triglycerides; - Circulating triglycerides measured using routine laboratory methods at hospital | [underlined: Intermediate outcomes:]; [underlined: Triglycerides]; Change over time, between groups:; Diet Cola < SSSD, P=0.0007 | TEI adjusted: Yes (Between-group differences NS at baseline or during study); Confounders accounted for:; - Key confounders: sex, age, anthropometry, smoking; - Other factors considered: total energy intake, medications, food form (beverage); Confounders NOT accounted for:; - Key confounders: race/ethnicity, SES, alcohol intake, physical activity, naturally occurring sugar intake; - Other factors considered: menopausal status, supplements, sodium, protein, fiber, fat, energy density, family history of CVD; Additional model adjustments:; - NS at baseline: liver fat, triglycerides, fasting plasma insulin, uric acid; Limitations:; - Randomization and allocation methods NR; - No power calculation and likely underpowered; - Trial registry did not include data analysis plan; Funding Sources:; Danish Council for Strategic Research; The Food Study Group/Danish Ministry of Food, Agriculture and Fisheries; Novo Nordic Foundation; Clinical Institute at Aarhus University, Denmark; Danish Dairy Company, Arla Foods
Engel, 2018 (https://pubmed.ncbi.nlm.nih.gov/29235560-effect-of-high-milk-and-sugar-sweetened-and-non-caloric-soft-drink-intake-on-insulin-sensitivity-after-6-months-in-overweight-and-obese-adults-a-randomized-controlled-trial/) ^5^; RCT, Denmark; Baseline N=73, Analytic N=60; Attrition: 18%; Power: none, as the outcome (OGTT) was secondary and explorative; Recruitment: healthy, nondiabetic participants from two study sites at Aarhus University Hospital and University of Copenhagen; Participant characteristics: overweight and obese adults; - Sex (female): 67%; - Age: ~38y; - Race/ethnicity: NR; - SES: NR; - Anthropometrics: BMI ~32 kg/m^2^; - Physical activity: ≤10hr/wk (inclusion criteria); - Smoking: 100% non-smokers (inclusion criteria); Summary of findings:; Among overweight and obese adults, those who consumed SSSD every day for 6mo had increased total cholesterol and triacylglyercol compared to NCSD consumers. SSSD consumers did not differ in changes of LDL, HDL, Total:HD cholesterol, or systolic and diastolic blood pressure compared to NCSD consumers. | Intervention: Sugar-sweetened soft drink (SSSD); specifically, 1 L/d of sucrose-sweetened regular cola (50% glucose and 50% fructose), n=14; Comparator: Artificially sweetened non-caloric soft drink (NCSD); specifically, 1 L/d of aspartame-sweetened diet cola, n=15; Other interventions: semi-skimmed milk (n=15) and still mineral water (n=16); [underlined: Intervention duration]: 6mo; [underlined: Intervention compliance]: all participants were instructed to bring back empty bottles/cartons for monitoring compliance; Study added sugars intake:; - NR; Outcome assessment methods/timing:; - At baseline, and 6mo follow-up; - Intermediate outcomes measured: Total cholesterol, LDL, HDL, Total:HDL, triacylglycerol, systolic and diastolic blood pressure; - Fasted blood samples collected; Total and HDL cholesterol, and triacylglycerol analyzed using routine laboratory methods at hospital and LDL cholesterol calculated by Friedewald equation; blood pressure recorded with digital blood pressure apparatus after 10min rest | [underlined: Intermediate outcomes:]; [underlined: Total cholesterol], mmol/L, Mean (SE); Within group, over time: 0mo, 6mo; NCSD: 5.45 (0.84), 4.95 (0.18); SSSD: 4.84 (0.84), 5.25 (0.28); Between groups: P=0.007; [underlined: LDL cholesterol], mmol/L, Mean (SE); Within group, over time: 0mo, 6mo; NCSD: 3.50 (0.98), 3.17 (0.18); SSSD: 3.07 (0.82), 3.32 (0.23); Between groups: P=NS; [underlined: HDL cholesterol], mmol/L, Mean (SE); Within group, over time: 0mo, 6mo; NCSD: 1.18 (0.29), 1.17 (0.07); SSSD: 1.16 (0.23), 1.21 (0.09); Between groups: P=NS; [underlined: Total:HDL cholesterol], mmol/L, Mean (SE); Within group, over time: 0mo, 6mo; NCSD: 4.83 (1.15), 4.41 (0.28); SSSD: 4.26 (0.80), 4.49 (0.24); Between groups: P=NS; [underlined: Triacylglycerol], mmol/L, Mean (SE); Within group, over time: 0mo, 6mo; NCSD: 1.73 (0.63), 1.37 (0.11); SSSD: 1.35 (0.73), 1.60 (0.23); Between groups: P=0.045; [underlined: Systolic blood pressure], mmHg, Mean (SE); Within group, over time: 0mo, 6mo; NCSD: 131.5 (14.1), 126.8 (2.4); SSSD: 123.4 (8.9), 125.9 (2.9); Between groups: P=NS; [underlined: Diastolic blood pressure], mmHg, Mean (SE); Within group, over time: 0mo, 6mo; NCSD: 81.2 (7.9), 77.4 (2.3); SSSD: 74.4 (9.7), 77.5 (2.0); Between groups: P=NS | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, alcohol intake, physical activity, anthropometry, smoking; - Other factors considered: total energy intake, menopausal status, medications, supplements, protein, fat, food form (beverage); Confounders NOT accounted for:; - Key confounders: race/ethnicity, SES, naturally occurring sugar intake; - Other factors considered: menopausal status, supplements, sodium, fiber, energy density, family history of CVD; Additional model adjustments:; - NS at baseline: Carbohydrate, calcium, OGTT glucose and insulin, fasting glucose and insulin, Matsuda index, HOMA-IR, PAI-1, FFA; Limitations:; - No power calculation; - No information on non-completers; - No preregistered data analysis plan; Funding Sources: Arla Foods; Danish Dairy Research Foundation; Global Dairy Platform; Danish Agriculture and Food Foundation; Dairy Institute; Dairy Research Industry; Danish Agriculture and Food Council
Hernandez-Cordero, 2014 (https://pubmed.ncbi.nlm.nih.gov/25332472-substituting-water-for-sugar-sweetened-beverages-reduces-circulating-triglycerides-and-the-prevalence-of-metabolic-syndrome-in-obese-but-not-in-overweight-mexican-women-in-a-randomized-controlled-trial/) ^6^; RCT, Mexico; Baseline N=268, Analytic N=240; Attrition: 10%; Power: powered to observe a 31±58 mg/dL decrease in plasma [TG] and a weight loss of 1.8±3.4 kg; needed a sample size of 120 cases, which considered 2-sided tests, with 90% power, α=0.05, and allowed for >75% attrition; Recruitment: advertising campaign; Participant characteristics: Mexican women with overweight or obesity who habitually consumed ≥250 kcal/d of SSB; - Sex (female): 100%; - Age: 33.3 (6.7) y (18-45y); - Race/ethnicity: NR; - SES: 45% completed middle and high school; - Anthropometrics: 46% Overweight, 54% Obese; BMI 31.2 (3.7) kg/m^2^; - Physical activity: NR; - Smoking: 31% Yes; Summary of findings:; A 9-month lifestyle intervention to reduce SSB intake in Mexican women with overweight and obesity did not result in changes in plasma triglycerides or cholesterol (total, LDL, HDL), or systolic and diastolic blood pressure in the intervention group compared to control. | Intervention: Decreasing SSB intake (nutrition counseling sessions included activities to encourage increased water intake, reduced SSB intake, and substitution of water for SSBs; received bottled water every 2wk), n=120; Comparator: Control; education provision, n=120; [underlined: Intervention duration]: 9mo; [underlined: Intervention compliance]: Examined change in SSB intake using 3, 24-h recalls at baseline, 3, 6, and 9mo – SSB was significantly lower in both groups at 3, 6, and 9mo; Study added sugars intake:; - Habitual SSB intake ≥250 kcal/d (inclusion criteria); Outcome assessment methods/timing:; - At baseline, and 3, 6, 9mo follow-up; - Intermediate outcomes measured: Plasma triglycerides, total cholesterol, LDL, HDL, and systolic/diastolic blood pressure; - Fasting blood samples analyzed using standard laboratory procedures; resting blood pressure measured using digital sphygmomanometer (mean of 3 measurements used) | [underlined: Intermediate outcomes:]; [underlined: Triglycerides], mg/dL, Mean (SE); Within group, over time: ∆3, ∆6, ∆9mo; Control: 1.8 (6.6), 13.6 (11.3), 10.7 (9.90); Intervention: 5.6 (8.0), −2.4 (9.1), −5.7 (10.0); Between groups: P-interaction=NS; P=NS for all stages; [underlined: Total cholesterol], mg/dL, Mean (SE); Within group, over time: ∆3, ∆6, ∆9mo; Control: 5.7 (5.2), 1.2 (7.6), −3.0 (8.9); Intervention: 1.5 (4.7), 5.8 (5.6), 1.9 (8.7); Between groups: P-interaction=NS; P=NS for all stages; [underlined: LDL cholesterol], mg/dL, Mean (SE); Within group, over time: ∆3, ∆6, ∆9mo; Control: 4.6 (3.7), −1.6 (4.6), −5.0 (4.7); Intervention: 1.1 (3.5), 4.9 (4.0), 0.2 (4.0); Between groups: P-interaction=NS; P=NS for all stages; [underlined: HDL cholesterol], mg/dL, Mean (SE); Within group, over time: ∆3, ∆6, ∆9mo; Control: 1.20 (1.4), 1.1 (4.6), −1.7 (1.8); Intervention: −0.3 (1.3), 1.9 (8.5), 0.3 (1.40); Between groups: P-interaction=NS; P=NS for all stages; [underlined: Systolic blood pressure], mmHg, Mean (SE); Within group, over time: ∆3, ∆6, ∆9mo; Control: −1.3 (1.0), −3.8 (1.4), −2.8 (1.7); Intervention: 0.05 (0.09), −2.4 (1.0), −0.9 (1.2); Between groups: P-interaction=NS; P=NS for all stages; [underlined: Diastolic blood pressure], mmHg, Mean (SD); Within group, over time: ∆3, ∆6, ∆9mo; Control: −1.9 (0.8), −4.7 (1.1), −3.9 (1.5); Intervention: −1.0 (0.9), −3.7 (1.0), −3.4 (1.1); Between groups: P-interaction=NS; P=NS for all stages | TEI adjusted: Yes; [underlined: TEI], kcal/d, Mean (SE); Within group, over time: ∆3, ∆6, ∆9mo; Control: −447 (52), −478 (60), −567 (66); SSB: −553 (56), −575 (54), −585 (55); Between groups: P-interaction=NS; P=NS for all stages; Confounders accounted for:; - Key confounders: sex, age, (race/ethnicity), SES, physical activity, anthropometry, smoking; - Other factors considered: total energy intake, food form (beverage); Confounders NOT accounted for:; - Key confounders: alcohol intake, naturally occurring sugar intake; - Other factors considered: menopausal status, medications, supplements, sodium, protein, fiber, fat, energy density, family history of CVD; Additional model adjustments:; - NS at baseline: parity, marital status, fasting plasma glucose, HbA1c, serum and urine osmolality, beverages with sugar, water consumption, baseline intermediate outcomes; Limitations:; - Allocation methods NR; - No a priori analysis plan; Funding Source:; Danone Research Center
Madero, 2015 (https://pubmed.ncbi.nlm.nih.gov/26329473-a-pilot-study-on-the-impact-of-a-low-fructose-diet-and-allopurinol-on-clinic-blood-pressure-among-overweight-and-prehypertensive-subjects-a-randomized-placebo-controlled-trial/) ^7^; RCT, Mexico; Baseline N=78, Analytic N=72; Attrition: 3%; Power: post hoc calculations of power analyses made with the differences found in SBP and DBP among allopurinol and placebo groups yielded in a power of 94%; Recruitment: clinic; Participant characteristics: overweight, prehypertensive adults; - Sex (female): 39%; - Age: 46 (8) y; - Race/ethnicity: NR; - SES: NR; - Anthropometrics: all overweight; mean ~88kg; - Physical activity: NR; - Smoking: NR; Summary of findings:; There were no differences between groups of overweight prehypertenisive adults that were on a low-fructose and sodium diet or a low sedum diet for 4 weeks for any CVD outcomes: blood pressure, total cholesterol, and triglycerides. | Intervention: Low fructose (<20g/d) and sodium diet (<2500mg/d); n= 34; Comparator: Low sodium diet (<2500mg/d); n=38; [underlined: Intervention duration]: 4wks; [underlined: Intervention compliance]: Adherence was defined as attending at least 80% of the scheduled clinic visits and having blood work during this last visit; fructose intake decreased significantly in low fructose group (P<0.05 within and between groups); Study added sugars intake:; - Inclusion criteria: history of high fructose consumption from sources of added sugar (excluding fruits) of >70 g/d.; Outcome assessment methods/timing:; - Baseline, 4wks; - Intermediate outcomes measured: Total cholesterol, Triglycerides, Systolic and diastolic BP (3 BP measures: clinic, global-ABPM, Day-ABPM); - ABPM: Ambulatory Blood Pressure Monitoring | [underlined: Intermediate outcomes:]; [underlined: Blood pressure]: mm Hg, Mean (SD); - [underlined: Clinic SBP]; Within group, over time: 0wks, 4wks; Control: 125 (11), 120 (11), P<0.05; Low fructose: 124 (13), 119 (13), P<0.05; Between groups: NS; - [underlined: Clinic DBP]; Within group, over time: 0wks, 4wks; Control: 86 (7), 82 (10), P<0.05; Low fructose: 84 (8), 82 (8), P<0.05; Between groups: NS; - [underlined: Global SBP ABPM]; Within group, over time: 0wks, 4wks; Control: NS; Low fructose: NS; Between groups: NS; - [underlined: Global DBP ABPM]; Within group, over time: 0wks, 4wks; Control: NS; Low fructose: NS; Between groups: NS; - [underlined: Day SBP ABPM]; Within group, over time: 0wks, 4wks; Control: NS; Low fructose: NS; Between groups: NS; - [underlined: Day DBP ABPM]; Within group, over time: 0wks, 4wks; Control: NS; Low fructose: 83 (8), 81 (8), P<0.05; Between groups: NS; [underlined: Total cholesterol], mg/dL, Mean (SD); Within group, over time: 0wks, 4wks; Control: NS; Low fructose: NS; Between groups: NS; [underlined: Triglycerides], mg/dL, Mean (SD); Within group, over time: 0wks, 4wks; Control: NS; Low fructose: NS; Between groups: NS | TEI adjusted: No (control group significantly increased TEI during intervention; NS with intervention group); Confounders accounted for:; - Key confounders: sex, age, anthropometry; - Other factors considered: medications; Confounders NOT accounted for:; - Key confounders: race/ethnicity, SES, alcohol intake, physical activity, smoking, naturally occurring sugar intake; - Other factors considered: total energy intake, menopausal status, supplements, sodium, protein, fiber, fat, energy density, family history of CVD, food form (solid/beverage); Additional model adjustments:; - Fructose intake (g/24hr), fructose intake without fruits (g/24hr); Limitations:; - Not all key confounders accounted for; - No a priori power calculation; - Trial registry did not include data analysis plan; Funding Sources:; NR
Markey, 2016 (https://pubmed.ncbi.nlm.nih.gov/26349919-energy-compensation-following-consumption-of-sugar-reduced-products-a-randomized-controlled-trial/) ^8^; Crossover RCT, reformulated foods (REFORM) study, UK; Baseline N=56, Analytic N=50; Attrition: 1%; Power: n=37 participants to give sufficient power to detect significant changes in our secondary outcome measures including biochemical analysis, if energy compensation did not occur, with P < 0.05 and 80 % power; Recruitment: local community of Reading, UK using targeted mailings to volunteers on local participant databases; posters and flyers circulated around university campus and social/community groups in Reading; Participant characteristics: healthy normal or overweight adults; - Sex (female): 68/%; - Age: ~ 32y; - Race/ethnicity: 80% white; - SES: NR; - Anthropometrics: BMI ~24 kg/m^2^; - Physical activity: exclude participants of regular vigorous exercise or fitness training (≥20 min × 3 times/week); - Smoking: 100% non-smokers; Summary of findings:; In healthy normal and overweight adults, compared to a regular diet, substituting at least one food and beverage per day with a reduced-sugar version for 8 weeks did not affect CVD-related outcomes, including systolic and diastolic blood pressure, total cholesterol, HDL, LDL, or triglycerides. | Intervention: Reformulated/sugar-reduced diet: participants exchanged ≥1 beverage and ≥1 food portion per day from their habitual diet [underlined: with equivalent sugar-reformulated products]; foods provided by researchers; n=54; Comparator: Regular diet: participants exchanged ≥1 beverage and ≥1 food portion per day from their habitual diet [underlined: with equivalent sugarcontaining products]; foods provided by researchers; n=55; [underlined: Intervention duration]: 8wk per arm; 4wk washout between arms; [underlined: Intervention compliance]: 4d weighted food diaries; As a % EI, carbohydrate (P < 0.001), total sugars (P < 0.001) and NMES (P < 0.001) were lower, whereas fat (P = 0.001) and protein (P = 0.038) were higher on the sugar-reduced diet compared with the regular diet; Study added sugars intake: NR; Outcome assessment methods/timing:; - Before and after each arm: 0 and 8wks, 12 and 20wks; - Intermediate outcomes measured: total cholesterol (TC), HDL, LDL (calculated), Triglycerides (TG), Blood Pressure (SBP, DBP) | [underlined: Intermediate outcomes:]; [underlined: Supine SBP], mm Hg, Mean (SD); Within group, over time: 0wks, 8wks; Regular diet: NS; Reformulated diet: NS; Between groups (diet): NS; Time*diet: NS; [underlined: Supine DBP], mm Hg, Mean (SD); Within group, over time: 0wks, 8wks; Regular diet: NS; Reformulated diet: NS; Between groups (diet): NS; Time*diet: NS; [underlined: TC], mmol/L, Mean (SD); Within group, over time: 0wks, 8wks; Regular diet: 4.67 (0.70), 4.59 (0.65); Reformulated diet: 4.57 (0.69), 4.58 (0.67); Between groups (diet): NS; Time*diet: P= 0.021; [underlined: HDL-C], mmol/L, Mean (SD); Within group, over time: 0wks, 8wks; Regular diet: 1.54 (0.38), 1.51 (0.38); Reformulated diet: 1.50 (0.37), 1.51 (0.34); Between groups (diet): NS; Time*diet: P= 0.067; [underlined: LDL-C], mmol/L, Mean (SD); Within group, over time: 0wks, 8wks; Regular diet: NS; Reformulated diet: NS; Between groups (diet): NS; Time*diet: NS; [underlined: TG], mmol/L, Mean (SD); Within group, over time: 0wks, 8wks; Regular diet: NS; Reformulated diet: NS; Between groups (diet): NS; Time*diet: NS | TEI adjusted: No; Confounders accounted for:; - Key confounders: smoking; - Other factors considered: N/A; Confounders NOT accounted for:; - Key confounders: sex, age, race/ethnicity, SES, alcohol intake, physical activity, anthropometry, naturally occurring sugar intake; - Other factors considered: total energy intake, menopausal status, medications, supplements, sodium, protein, fiber, fat, energy density, family history of CVD, food form (solid/beverage); Additional model adjustments: N/A; Limitations:; - Trial registry did not include data analysis plan; Funding Sources:; Sugar Nutrition UK
Umpleby, 2017 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC6365592/) ^9^; RCT, Crossover design (Control group only – other group all had NAFLD), UK; Baseline N=27, Analytic N=25; Attrition: 7.4%; Power: NR (discussion states sample size was originally powered to assess weight-adjusted differences in all outcome variables); Recruitment: NR; Participant characteristics: overweight men at increased cardio-metabolic risk; - Sex (female): 0% (100% male); - Age: 59y (49-64y); - Race/ethnicity: NR; - SES: NR; - Anthropometrics: BMI ~28.7 kg/m^2^ (25-30 kg/m^2^); - Physical activity: NR (instructed to maintain normal level); - Smoking: 100% non-smokers; Summary of findings:; In a sample of overweight men at increased cardio-metabolic risk, a 12-wk high- or low-sugar diet did not significantly affect plasma concentrations of total cholesterol, LDL, or HDL. The effect was not significant within group (between the two different diets) or between groups with varying levels of liver fat (NAFLD vs. Control). A high-sugar diet was significantly associated with an increase in plasma TAG in the NAFLD group compared to control. | 2-way crossover design: 2, 12-wk dietary interventions; High-sugar diet: corresponded to the top 2.5^th^ percentile of non-milk extrinsic sugars (NMES) intake in the UK population (i.e., NMES includes free sugars added to food (including 50% of sugars in tinned and dried fruit), but excludes sugars in whole fruit, and lactose); Low-sugar diet: corresponded to the lower 2.5^th^ percentile of NMES intake [underlined: Method]: diets were achieved by a dietary exchange of sugars for starch using commercially available foods (isoenergetic and equal macronutrient distribution); Control group: n=14; [underlined: Intervention duration]: Crossover design: 4wk run in period, 12wk per intervention arm with a 4wk washout period between; [underlined: Intervention compliance]: Self-recorded dietary intakes were monitored by regular home visits and indicated compliance was maintained; 3-d diet diaries were also completed during final week of each intervention; Outcome assessment methods/timing:; - Measured at beginning and end of each intervention arm; - Intermediate outcomes measured: Total cholesterol, LDL, HDL, TAG | [underlined: Intermediate outcomes:]; [underlined: Plasma TAG], mmol/l, Mean (SEM); Within group, High sugar vs. Low sugar:; Control (n=14): 1.33 (0.15) vs 1.13 (0.08), NS; [underlined: Plasma cholesterol], mmol/l, Mean (SEM); Within group, High sugar vs. Low sugar:; Control (n=14): NS; [underlined: Plasma LDL-C], mmol/l, Mean (SEM); Within group, High sugar vs. Low sugar:; Control (n=14): NS; [underlined: Plasma HDL-C], mmol/l, Mean (SEM); Within group, High sugar vs. Low sugar:; Control (n=14): NS; [Effects of intervention on plasma lipoprotein fraction concentrations, lipoprotein kinetics and de novo lipogenesis, palmitate kinetics, post-heparin lipase, and plasma apoproteins are also provided in paper.] | TEI adjusted: Diets were isocaloric; Confounders accounted for:; - Key confounders: no baseline differences in sex, age, or smoking; body weight adjusted in all models; - Other factors considered: total energy intake, lipid-lowering medication; Confounders NOT accounted for:; - Key confounders: race/ethnicity, SES, alcohol intake, physical activity, naturally occurring sugar intake; - Other factors considered: other medications, supplements, sodium, protein, fiber, fat, energy density, family history of CVD, food form (solid/beverage); Additional model adjustments: N/A; Limitations:; - Not all key confounders accounted for; - No details on power calculation; - Trial registry did not include data analysis plan; Funding Sources:; UK government grant from the Biological Biotechnology Scientific Research Council; University of Surrey PhD scholarship; Medical Research Council (body composition measurements); and infrastructure support from the National Institute of Health Research at the Cambridge Biomedical Research Centre.
Prospective Cohort Studies
Barrington, 2016 (https://pubmed.ncbi.nlm.nih.gov/27338763-mortality-outcomes-associated-with-intake-of-fast-food-items-and-sugar-sweetened-drinks-among-older-adults-in-the-vitamins-and-lifestyle-vital-study/) ^10^; Prospective Cohort Study, Vitamins and Lifestyle (VITAL) study, United States; Analytic N=69582; Power: NR; Recruitment: names of residents in Western Washington State acquired through purchased mailing lists; Participant characteristics: older adults; - Sex (female): 51%; - Age: 47% 50-59y, 35% 60-69y, 18% 70-76y; - Race/ethnicity: 93% White; - SES: 43% ≥College graduate; - Anthropometrics: NR; - Physical activity: NR; - Smoking: NR; Summary of findings:; Among older adults, added sugars from sugar-sweetened drink intake was not significantly associated with risk of CVD-specific mortality | Exposure of interest: Sugar-sweetened drink intake (SSD selected a priori and included servings of sugar-sweetened soda (not diet), fruit drinks not including juice (e.g., Hi-C, Gatorade, lemonade) and cranberry juice, which is highly sweetened); Comparators: SSD intake (categorical, svg/wk); - Quartile 1: 0-0.1 svg/wk; - Quartile 2: 0.2-0.4 svg/wk; - Quartile 3: 0.5-2.7 svg/wk; - Quartile 4: ≥2.8 svg/wk; [underlined: Exposure assessment method and timing]:; - Semi-quantitative FFQ representing diet over the year previous to baseline; - At baseline; Outcome assessment methods/timing:; - 1yr post-baseline through December 31, 2008 (mean 6.9yr follow-up); - Health outcomes measured: death from CVD; - Cause of death obtained through Washington State death records using codes of the ICD, 10^th^ Revision (CVD codes: I00-I99) | [underlined: Endpoint outcomes:]; [underlined: Death from CVD (n=1066):] By quartiles of SSD drink, Cox proportional hazards, HR (95% CI); Total: P-trend=NS; No CVD history (n=192): P-trend=NS; CVD history (n=874): P-trend=NS; P-interaction=NS | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, race/ethnicity, SES, alcohol intake, physical activity, smoking; - Other factors considered: total energy intake, anthropometry, medications, sodium, protein, fiber, fat, energy density, family history of CVD, food form (beverage); Confounders NOT accounted for:; - Key confounders: naturally occurring sugar intake; - Other factors considered: menopausal status, supplements, sodium, protein, fiber, fat, energy density; Additional model adjustments: Self-rated health, mammogram (females), prostrate-specific antigen screening (males), sigmoidoscopy, servings of fruits and vegetables, estrogen or estrogen+progestin therapy (females); Limitations:; - Not all key confounders accounted for; - No information on non-completers; - Validation of exposure data collection tool unclear; - Exposure data only measured at baseline; - No preregistered data analysis plan; - Generalizability: sample mostly white, educated, older adults; Funding sources:; NCI; Office of Dietary Supplements
Collin, 2019 (https://pubmed.ncbi.nlm.nih.gov/31099861-association-of-sugary-beverage-consumption-with-mortality-risk-in-us-adults-a-secondary-analysis-of-data-from-the-regards-study/) ^11^; Prospective Cohort Study, Reasons for Geographic and Racial Differences in Stroke (REGARDS) study, United States; Analytic N=13440; Overall cohort attrition: 25%; Power: NR; Recruitment: mail and telephone; participants randomly selected using commercially available lists of US residents with goal of recruiting half of study sample from the stroke buckle (coastal North and South Carolina and some parts of Georgia) and the stroke belt (remaining areas of North Carolina, South Carolina, Georgia, Tennessee, Mississippi, Alabama, Louisiana, and Arkansas) and other half from the rest of the United States; Participant characteristics: adults; - Sex (female): 41%; - Age: 63.6 (9.1) y (all >40y); - Race/ethnicity: 69% White, 31% Black; - SES: Education, 31% ≤High school, 41%≥College; - Anthropometrics: 71% Overweight or Obesity; - Physical activity: 30%, 0 times/wk; 31% >4 times/wk; - Smoking: 48% Never; 38% Former; 13% Current; Summary of findings:; Among adults, added sugars from sugary beverages, SSBs, and 100% fruit juice intake (combined and separate) was not significantly associated with risk of CHD-related mortality. | Exposure of interest: Sugary beverage intake (including SSBs (sodas, soft drinks, or fruit-flavored drinks) and naturally sweet 100% fruit juices); 12-oz serving; Comparators:; - Continuous; 12-oz/svg; - Categorical; % of TEI intake; ○ Low: <5%; ○ Medium: 5-<10%; ○ High: ≥10%; [underlined: Exposure assessment method and timing]:; - Validated semi-quantitative FFQ; represents usual dietary intake over the past year; - At baseline enrollment (2003-2007); Outcome assessment methods/timing:; - Follow-up every 6mo through 2013; - Health outcomes measured: CHD-related mortality; - Cause of death obtained through medical records, death certificates, National Death Index, Social Security Administration Master Death File, and interviews with family members; adjudication done by clinicians (general internists, cardiologists, and physician assistants) with specific training to identify causes of death | [underlined: Endpoint outcomes:]; [underlined: CHD-related mortality:]; Change per 12 oz increase, Cox proportional hazards, HR (95% CI); All sugary beverages: P=NS; SSBs: P=NS; Fruit juices: P=NS; For sugary beverages, SSBs, and fruit juices: NS interaction by age, sex, education, or race/ethnicity; Change per intake level of sugary beverages, HR (95% CI); <5% TEI (ref) vs; 5-<10% TEI: P=NS with TEI unadj and adj; ≥10% TEI: P=NS with TEI unadj and adj; Examining SSBs and fruit juices separately did not change the results | TEI adjusted: Yes and No; Confounders accounted for:; - Key confounders: sex, age, race/ethnicity, SES, alcohol intake, physical activity, smoking; - Other factors considered: total energy intake, anthropometry, fiber, fat, food form (beverage); Confounders NOT accounted for:; - Key confounders: naturally occurring sugar intake; - Other factors considered: menopausal status, medications, supplements, sodium, protein, energy density, family history of CVD; Additional model adjustments: Diet; Limitations:; - Not all key confounders accounted for; - Non-completers more likely to be female, non-Hispanic black, have overweight/obesity, be former or current smokers, and have less than high school education; - Exposure data only measured once; - No preregistered data analysis plan; Funding sources:; NINDS; NIH; NHLBI
Kulezic, 2019 (https://pubmed.ncbi.nlm.nih.gov/31431146-healthy-diet-and-fiber-intake-are-associated-with-decreased-risk-of-incident-symptomatic-peripheral-artery-disease-a-prospective-cohort-study/) ^12^; Prospective Cohort Study, Malmö Diet and Cancer Study (MDCS), Sweden; Analytic N=26010; Power: NR; Recruitment: community directed (passive) invitation, and a personal letter of invitation (active recruitment); Participant characteristics: middle-aged adults; - Sex (female): 62%; - Age: ~58y; - Race/ethnicity: NR; - SES: University degree ~15%; - Anthropometrics: BMI~25.6 kg/m^2^; - Physical activity: Leisure time physical activity >50 MET-hr/wk, 15%; - Smoking: 39% Never, 28% Current; Summary of findings:; In middle-aged Swedish adults, non-adherence to recommended sucrose intake (>10% energy) was not significantly associated with incidence of peripheral artery disease at ~21yr follow-up. | Exposure of interest: Sucrose intake; Comparators: categorical (based on adherence to Swedish dietary guidelines and nutrition recommendations for sucrose); - ≤10% energy (adherence); - >10% energy (non-adherence); [underlined: Exposure assessment method and timing]:; - 7-d food diary combined with a food questionnaire and 1hr interview (methods showed good ranking validity when compared to reference method); - At baseline; Outcome assessment methods/timing:; - At follow-up (median 21.7y, IQR 18.7-23.4y); - Health outcomes measured: Peripheral artery disease (PAD); PAD incidence determined using Inpatient and Outpatient Registers, which included information on date of admission and discharge, and diagnostic and procedural codes from all hospitalizations in Sweden; validation of PAD diagnosis done in 100 randomly selected patients, with confirmed diagnosis in 98% of cases | [underlined: Endpoint outcomes:]; [underlined: PAD Incidence], Based on adherence to diet quality index for sucrose, HR (95% CI); Non-adherence (>10% energy): Ref; Adherence (≤10% energy): 1.10 (0.96, 1.27); Similar results were obtained in sensitivity analysis, which was performed after removing misreporters (n=4799) and dietary-changers (n=5623) | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, SES, alcohol intake, physical activity, smoking; - Other factors considered: total energy intake, anthropometry, fiber, fat; Confounders NOT accounted for:; - Key confounders: race/ethnicity, naturally occurring sugar intake; - Other factors considered: menopausal status, medications, supplements, sodium, protein, energy density, family history of CVD, food form (solid/beverage); Additional model adjustments: Diet assessment method, season, fish and shellfish, fruit and vegetables; Limitations:; - Not all key confounders accounted for; - Exposure data only measured once; - No preregistered data analysis plan; Funding sources:; None
Liu, 2018 (https://pubmed.ncbi.nlm.nih.gov/29188817-dietary-sugar-intake-was-associated-with-increased-body-fatness-but-decreased-cardiovascular-mortality-in-chinese-elderly-an-11-year-prospective-study-of-mr-and-ms-os-of-hong-kong/) ^13^; Prospective Cohort Study, Mr and Ms OS of Hong Kong, Hong Kong; Analytic N=3416; Power: NR; Recruitment: notices in senior social centers and housing estates; Participant characteristics: Chinese older adults (≥65y); - Sex (female): 50%; - Age: ~72.5y; - Race/ethnicity: 100% Chinese; - SES: 10% ≥University education; - Anthropometrics: BMI ~23.5 kg/m^2^; - Physical activity: PASE score ~92; - Smoking: 7% Current smokers; Summary of findings:; Among Chinese elderly, compared with those in the lowest quintile of added sugar intake, participants with the highest quintile intake had a significantly lower risk of CVD mortality at ~11yr follow-up. Results were no longer significant after adjustment for adiposity. | Exposure of interest: Added sugar intake (caloric sweeteners, monosaccharides and disaccharides, added to foods/beverages during processing or preparation, including sugars and syrups added at table); Comparators: quintiles (% of energy); [underlined: Exposure assessment method and timing]:; - Validated FFQ; represents intake (portion size & frequency) during past 12mo; - At baseline; Outcome assessment methods/timing:; - At follow-up (mean 11.1yr); - Health outcomes measured: CVD mortality; - Data on mortality obtained from the Death Registry of the Department of Health of Hong Kong; CVD mortality identified by cause of death on death certificate and classified according to ICD version 10 | [underlined: Endpoint outcomes:]; [underlined: CVD mortality], HR (95% CI); Added sugar intake (% calories); Q1 (ref); Q2: 0.752 (0.307, 1.845); Q3: 0.323 (0.104, 1.006); Q4: 0.445 (0.156, 1.271); Q5: 0.251 (0.070, 0.899); P for trend: 0.011 (P=0.055 after further adjustment for change in body fatness); Added sugar from beverages (% calories); Q1 (ref); Q2: 0.923 (0.370, 2.303); Q3: 0.401 (0.127, 1.267); Q4: 0.376 (0.130, 1.085); Q5: 0.344 (0.109, 1.087); P for trend: 0.014 (P=0.074 after further adjustment for change in body fatness); Added sugar from cereals (% calories); P for trend: NS (data in paper); Added sugar from milk (% calories); P for trend: NS (data in paper); Added sugar from sweets (% calories); P for trend: NS (data in paper) | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, (race/ethnicity), SES, alcohol intake (in adults), physical activity, smoking,; - Other factors considered: total energy intake, anthropometry, medications, protein, fat, family history of CVD, food form (solid/beverage); Confounders NOT accounted for:; - Key confounders: naturally occurring sugar intake; - Other factors considered: menopausal status, supplements, sodium, fiber, energy density; Additional model adjustments: Fruit and vegetable intake, red or processed meat, total American Heart Association score, coffee, green and Chinese tea, history of cancers; Limitations:; - Does not account for all key confounders; - No information on non-completers; - Exposure data only measured once; - No preregistered data analysis plan; Funding sources:; NIH; Research Grants Council
Malik, 2019 (https://pubmed.ncbi.nlm.nih.gov/30882235-long-term-consumption-of-sugar-sweetened-and-artificially-sweetened-beverages-and-risk-of-mortality-in-us-adults/) ^14^; Prospective Cohort Study, Nurses’ Health Study (NHS) + Health Professionals Follow-up Study (HPFS), United States; Analytic N=118363; Power: NR; Recruitment: convenience sample; Participant characteristics: adults; - Sex (female): 68%; - Age: mean ~ 60y, in 1994; - Race/ethnicity: ~96% white; - SES: NR; - Anthropometrics: BMI ~27 kg/m^2^; - Physical activity: NR; - Smoking: ~12% current smoker, in 1994; Summary of findings:; There is a significant association between increased frequency of SSB consumption and risk of CVD mortality. | Exposure of interest: SSBs (caffeinated colas, caffeine-free colas, other (non-cola) carbonated sugar-sweetened beverages, and noncarbonated sugar-sweetened beverages (fruit punches, lemonades, or other fruit drinks); does not include fruit juice; Comparators:; - SSB continuous (svg/d); - SSB categorical:; - <1/mo; - 1-4/mo; - 2-6/wk; - 1-<2/d; - ≥2/d; [underlined: Exposure assessment method and timing]:; - FFQ; validated; - At baseline, every ~4y; Outcome assessment methods/timing:; - 34y follow-up for NHS; 28y follow-up for HPFS; - Endpoint outcome: CVD-related death (ICD codes 390–458 in the NHS and 390–459 in the HPFS) | [underlined: CVD mortality], HR (95% CI); Change per 1 svg/d increment:; 1.10 (1.06, 1.14); Change by SSB category:; <1/mo (ref) vs; 1-4/mo: 1.06 (1.00, 1.12); 2-6/wk: 1.10 (1.04, 1.17); 1-<2/d: 1.19 (1.08, 1.31); ≥2/d: 1.31 (1.15, 1.50); P for trend: <0.0001; Estimates were greater in NHS compared to HPFS but no interaction with sex was observed (P interaction=0.70) | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, race/ethnicity, alcohol, physical activity, smoking; - Other factors considered: total energy intake, anthropometry, medications (aspirin), supplements, family history of CVD (myocardial infarction), food form (beverage); Confounders NOT accounted for:; - Key confounders: SES, naturally occurring sugar intake; - Other factors considered: menopausal status, medications, sodium, protein, fiber, fat, energy density; Additional model adjustments: Postmenopausal hormone use (NHS), family history of diabetes, family history of cancer, baseline history of hypertension and hypercholesterolemia, intake of whole grains, fruit, vegetables, red and processed meat, artificially sweetened beverages; Limitations:; - Not all key confounders accounted for; - No preregistered data analysis plan; Funding sources:; NIH
Mullee, 2019 (https://pubmed.ncbi.nlm.nih.gov/31479109-association-between-soft-drink-consumption-and-mortality-in-10-european-countries/) ^15^; Prospective Cohort Study, European Prospective Investigation into Cancer and Nutrition (EPIC), Denmark, France, Germany, Greece, the Netherlands, Norway, and the United Kingdom; Analytic N=202,907; Power: NR; Recruitment: convenience sample; Participant characteristics: adults; - Sex (female): 71%; - Age: ~ 51y; - Race/ethnicity: NR; - SES: ~25% higher education; - Anthropometrics: BMI ~24 kg/m^2^; - Physical activity: ~20% physically active; - Smoking: current smokers ~23%; Summary of findings:; There was not a significant association between sugar-sweetened soft drink consumption and mortality from circulatory diseases or ischemic heart disease. | Exposure of interest: Sugar-sweetened soft drink consumption; 1 glass = 250 mL; Comparators: categorical; - <1 glass/mo (ref); - 1-4 glasses/mo; - >1-6 glasses/wk; - 1-<2 glasses/d; - ≥2 glasses/d; [underlined: Exposure assessment method and timing]:; - Self-administered questionnaires were used in all centers, except in Greece, Spain, and Ragusa (Italy), where data were collected during personal interviews. In Malmö (Sweden), a combined semi-quantitative food frequency questionnaire and 7-day dietary diary and diet interview was used4-d dietary record completed by parents; represents dietary intake on both weekdays and weekends; validated for some countries; - At baseline; Outcome assessment methods/timing:; - Mean follow-up time: 16.4y; - Endpoint outcome: circulatory disease mortality, ischemic heart disease mortality; - Ischemic heart disease (ICD-10 codes I20-I25) grouped within “Circulatory diseases” (ICD-10 codes I00-I99) | [underlined: Circulatory diseases mortality], HR (95% CI), P-trend: Sexes combined: NS; Men only: NS; Women only: NS; [underlined: Ischemic heart disease mortality], HR (95% CI); P-trend: NS; Sensitivity analysis excluding BMI from multivariable models are in the paper. | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, SES, alcohol intake, physical activity, smoking; - Other factors considered: total energy intake, anthropometry, menopausal status; Confounders NOT accounted for:; - Key confounders: race/ethnicity, naturally occurring sugar intake; - Other factors considered: medications, supplements, sodium, protein, fiber, fat, energy density, family history of CVD; Additional model adjustments: Use of contraceptive pill, use of menopausal hormone therapy, red and processed meat, fruits and vegetables, coffee, and fruit and vegetable juice, study center, artificially sweetened soft drinks; Limitations:; - Not all key confounders accounted for; - Exposure data collection tool differed between sites, sometimes not validated; - Exposure data only measured once; - No preregistered data analysis plan; Funding sources: European Commission, the International Agency for Research on Cancer; IARC-Ireland Postdoctoral Research Training Fellowship from the Irish Cancer Society
Nagata, 2019 (https://www.cambridge.org/core/journals/british-journal-of-nutrition/article/intake-of-starch-and-sugars-and-total-and-causespecific-mortality-in-a-japanese-community-the-takayama-study/8AB0BC98C6CA4354C0EB5F9BAB6F96C5) ^16^; Prospective Cohort Study, Takayama Study cohort, Japan; Analytic N=27079; Power: the sample size and number of total deaths were sufficiently large to detect an HR of 1·2 (or 0·83) for the highest quartile of intake as compared with the lowest, with a statistical power of 80% and significance level of 5%.; Participant characteristics: adults; - Sex (female): 58%; - Age: ~54y; Summary of findings:; There was a significant association between added sugars intake and increased risk of CVD mortality in men, but not in women. | Exposure of interest: Added sugars; Due to the lack of free sugar values in the database, all sugars in sugar, honey, starch sugar, soft drinks, juices, soya beverages, jams, confectioneries (including traditional confectioneries, cakes, buns, pastries, desserts, biscuits, snacks, candies, chocolates), ice cream, meat and seafood seasoned with sugar, yeast, bread and breakfast cereals were summed up to yield the intake of free sugars. According to the definition by the WHO, ‘100 % fruit juices’ was considered as free sugars. Conversely, naturally occurring sugars in fruit and vegetables or dairy products were not included. Intake of naturally occurring sugars was estimated by subtracting the free sugar intake from the total sugar intake; Comparators: categorical, quartiles; [underlined: Exposure assessment method and timing]:; - Validated FFQ; - At baseline; Outcome assessment methods/timing:; - Mean follow-up time: 14.1y; - Endpoint outcomes: CVD deaths (ICD-10: I00–I99) | [underlined: CVD mortality], HR (95% CI); Men: p-trend= 0.0002; Q1: 1.0; Q2: 0.89 (0.72, 1.10); Q3: 1.21 (0.98, 1.50); Q4: 1.37 (1.10, 1.71); Women: NS | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, (race/ethnicity), SES, alcohol intake, physical activity, smoking, naturally occurring sugar intake; - Other factors considered: total energy intake, anthropometry, sodium, fiber, fat; Confounders NOT accounted for:; - Key confounders: N/A; - Other factors considered: menopausal status, medications, supplements, protein, energy density, family history of CVD, food form (solid/beverage); Additional model adjustments: Coffee, history of diabetes and hypertension; Limitations:; - Exposure data only measured once; - No preregistered data analysis plan; Funding sources:; Ministry of Education, Culture, Sports, Science, and Technology, Japan
Odegaard, 2015 (https://pubmed.ncbi.nlm.nih.gov/25733477-beverage-habits-and-mortality-in-chinese-adults/) ^17^; Prospective Cohort Study, Singapore Chinese Health Study, Singapore; Analytic N=63257; Power: NR; Participant characteristics: adults; - Sex (female): ~56%; - Age: ~ 56y; Summary of findings:; There was not a significant association between soft drink intake or juice and risk of CVD-related mortality. | Exposure of interest 1: Soft drink intake; Exposure of interest 2: Juice intake (unclear if 100%); Comparators: categorical; - None; - Monthly; - 1/wk; - ≥2/wk; [underlined: Exposure assessment method and timing]:; - FFQ interview; intake during past year; focused on frequency not amount; validated; - At baseline (1993-1998); Outcome assessment methods/timing:; - ~13-18y follow-up; - Endpoint outcomes: deaths from cardiovascular disease (ICD-9 codes 394.0–459.0) | [underlined: CVD Mortality], HR (95% CI), P-trend:; Soft drink: NS; Juice: NS | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, SES, physical activity, smoking; - Other factors considered: total energy intake, anthropometry; Confounders NOT accounted for:; - Key confounders: race/ethnicity, alcohol intake, naturally occurring sugar intake; - Other factors considered: menopausal status, medications, supplements, sodium, protein, fiber, fat, energy density, family history of CVD, food form (solid/beverage); Additional model adjustments: Dialect, year of interview, sleep, hypertension, non-beverage vegetable-fruit-soy–rich dietary pattern score; Limitations:; - Not all key confounders accounted for; - Exposure not well-defined (frequency not amount); - Exposure data only measured once; - No preregistered data analysis plan; Funding sources:; NIH
Ogilvie, 2017 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5320408/) ^18^; Prospective Cohort Study, Atherosclerosis Risk in Communities Study (ARIC), United States; Analytic N=14082; Power: NR; Recruitment: NR; Participant characteristics: adults; - Sex (female): 55%; - Age: ~54y (45-64y); - Race/ethnicity: 74% white; - SES: >high school: ~36%; - Anthropometrics: NR; - Physical activity, 1-5 scale: ~2.5; - Smoking, current: ~26%; Summary of findings:; Sugar-sweetened beverage consumption was associated with lower risk of peripheral artery disease. | Exposure of interest: SSBs (regular soda and fruit drinks); [underlined: Exposure assessment method and timing]:; - FFQ, modification of validated version; - At baseline only; Outcome assessment methods/timing:; - Follow-up visits ~6y & ~9y after baseline; - Health outcomes measured: Incident peripheral artery disease; - Defined by a new ABI measure of <0.90 at either visit 3 or 4, or a hospital discharge diagnosis of PAD, a leg amputation, or a leg revascularization procedure (leg endarterectomy, aorto-iliac-femoral bypass surgery, or leg bypass surgery) through 2012 | [underlined: Peripheral artery disease (PAD)], Cox proportional hazard regression, HR (95% CI) (n=events/total participants); SSB, servings:; - Almost never (n=506/4440): Ref; - 1-3/mo (n=169/1611): 0.87 (0.73, 1.04); - 1/wk (233/2069): 0.89 (0.76, 1.05); - 2-6/wk (283/2822): 0.74 (0.63, 0.86); - ≥1/d (377/3136): 0.86 (0.73, 1.00); P-trend = 0.005; The relationship was no longer significant when stratified by diabetes status at baseline | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, race/ethnicity, SES, physical activity, smoking, naturally occurring sugar intake (as dairy, fruit, refined and whole grains); - Other factors considered: total energy intake, anthropometry (health outcomes); Confounders NOT accounted for:; - Key confounders: alcohol intake (in adults),; - Other factors considered: menopausal status, medications, supplements, sodium, protein, fiber, fat, energy density, family history of CVD, food form (solid/beverage); Additional model adjustments: Field center, intake of meat, dairy, fruits, vegetables, whole grains, and refined grains; Limitations:; - Not all key confounders accounted for; - No information on non-completers; - Exposure data collection tool not validated; - Exposure data only measured at baseline; - No preregistered data analysis plan; Funding sources:; NHLBI
Pase, 2017 (https://www.ncbi.nlm.nih.gov/pmc/articles/PMC5405737/) ^19^; Prospective Cohort Study, Framingham Heart Study offspring cohort, United States; Analytic N=2888; Power: NR; Participant characteristics: adults; - Sex (female): ~55%; - Age: ~62y (all >45y); - Race/ethnicity: “absence of ethnic minorities”; - SES: No HS degree ~4%; - Anthropometrics: BMI: ~27 kg/m^2^; - Physical activity: ME, hr/d ~42; - Smoking, current: ~12%; Summary of findings:; In a cohort of US adults over 45y, sugar-sweetened soft drink intake was not significantly associated with greater risk of stroke or risk of ischemic stroke over ~10y. | Exposure of interest: Sugar-sweetened soft drinks (SSSD; high-sugar carbonated beverages such as cola); [underlined: Exposure assessment method and timing]:; - FFQ assessing avg intake over past year, validated; - Baseline (1991-1995—5^th^ assessment of overall Framingham Heart Study offspring cohort); - Follow ups at ~4y & ~8y (1998-2001),; - Average of the three assessments; Outcome assessment methods/timing:; - Starting at 8y assessment (1998-2001), ~10y follow up; - Health outcomes self-reported: Incident stroke, defined as the rapid onset of focal neurological symptoms of presumed vascular origin, lasting >24 hours or resulting in death; diagnosis of stroke determined by review committee that adjudicated after reviewing all available medical records, imaging studies, and neurological reports; - Ischemic stroke proportion also identified; - 97 cases of stroke (82 ischemic) | [underlined: Risk of Stroke], Cox proportional hazards regression, HR (95% CI); SSSD intake at last examination: P=NS; - 0/wk: Ref; - >0-3/wk: 1.15 (0.71, 1.88); - >3/wk: 0.69 (0.29, 1.62); SSSD intake avg of 3 measurements over ~8y: P=NS; - 0/wk: Ref; - >0-3/wk: 1.17 (0.70, 1.97); - >3/wk: 0.61 (0.25, 1.49); [underlined: Risk of Ischemic Stroke], Cox proportional hazards regression, HR (95% CI); SSSD intake at last examination: P=NS; - 0/wk: Ref; - >0-3/wk: 1.11 (0.65, 1.89); - >3/wk: 0.69 (0.27, 1.73); SSSD intake avg of 3 measurements over ~8y: P=NS; - 0/wk: Ref; - >0-3/wk: 1.12 (0.63, 1.99); - >3/wk: 0.61 (0.23, 1.61); Interactions between beverage consumption and waist to hip ratio, APOE ɛ4 allele status, and prevalent diabetes: results NS; Sensitivity analyses conducted:; - Prevalent hypertension; - Prevalent CVD; - Prevalent diabetes; - Waist to hip ratio; - Total cholesterol; - HDL cholesterol; None changed significance level of results | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, physical activity, smoking; - Other factors considered: total energy intake; Confounders NOT accounted for:; - Key confounders: race/ethnicity, SES, naturally occurring sugar intake, alcohol intake (in adults),; - Other factors considered: menopausal status, medications, supplements, sodium, protein, fiber, fat, energy density, food form (solid/beverage), anthropometry (health outcomes), family history of CVD; Additional model adjustments:; Diet quality (Dietary guidelines adherence index); Note: Model 3 (not extracted) adjusts for SBP, CVD, Afib, left ventricular hypertrophy, total cholesterol, HDL, diabetes, and waist to hip ratio but does not adjust for diet quality, physical activity, or smoking; Limitations:; - Not all key confounders accounted for; - No information on non-completers; - No preregistered data analysis plan; Funding sources:; National Health and Medical Research Council; NHLBI; NIA; NINDS; USDA ARS
Rahman, 2015 (https://heart.bmj.com/content/101/24/1961.abstract) ^20^; Prospective Cohort Study, Cohort of Swedish Men (COSM), Sweden; Analytic N=42400; Power: NR; Recruitment: All men born 1918-1952 and residing in Örebro and Västmanland counties in Sweden were asked to complete an extensive questionnaire; Participant characteristics: adults; - Sex (female): 0% (100% male); - Age: ~60y (45-79y); - Race/ethnicity: NR; - SES: University education ~15%; - Anthropometrics: Obesity: ~47%; - Physical activity: ME, hr/d ~42; - Smoking, ever: ~63%; Summary of findings:; In Swedish men, consuming two or more sweetened beverages per day was associated with a greater risk of heart failure compared to non-consumers over a follow up of ~12 years. | Exposure of interest: Sweetened beverages (defined as soft drinks and sweetened juice drinks; does not include fruit juice); 1 serving = 200mL; Comparators: Categorization by quartiles for consumers:; - No consumption: Ref; - 0.1-<0.5 svg/d; - 0.5-<1.0 svg/d; - 1.0-<2.0 svg/d; - ≥2.0 svg/d; [underlined: Exposure assessment method and timing]:; - FFQ assessing typical daily/weekly intake, validation unclear; - At baseline only; Added sugars intake at baseline:; - 0 svg/d: 50%; - 0.1-<0.5 svg/d: 17%; - 0.5-<1.0 svg/d: 7%; - 1.0-<2.0 svg/d: 13%; - ≥2.0 svg/d: 13%; Outcome assessment methods/timing:; - Avg follow up ~12y; - Health outcomes measured: Incident heart failure (HF); - Identified using Swedish National Patient Register and Cause of Death Register using International Classification of Diseases-10 codes I50 and I11.0; - Events identified as either the primary or secondary diagnosis of hospitalization or death were included; - 4113 events occurred (3604 first events HF hospitalizations and 509 HF deaths) | [underlined: Incident heart failure], Cox proportional hazards ratio, HR (95% CI); (n = number of cases at each intake level); SSB at baseline:; 0 svg/d (n=2123): Ref; 0.1-<0.5 svg/d (n=490): 0.98 (0.88, 1.08); 0.5-<1.0 svg/d (n=271): 1.08 (0.95, 1.23); 1.0-<2.0 svg/d (n=572): 1.09 (0.99, 1.20); ≥2.0 svg/d (n=657): 1.23 (1.12, 1.35); P for trend: <0.001; Smoking status, BMI, age >65y, and diabetes were examined as potential effect modifiers (interactions): Results NS; Sensitivity analyses conducted:; - Excluding HF events occurring in first 5y of follow up (reduce risk of reverse causality); - Exclude ppts with diabetes; - Exclude ppts with stroke; - Exclude ppts with angina; None changed significance level of results | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, SES, alcohol intake (in adults), physical activity, smoking; - Other factors considered: total energy intake, anthropometry (health outcomes), family history of MI; Confounders NOT accounted for:; - Key confounders: race/ethnicity, naturally occurring sugar intake; - Other factors considered: menopausal status, medications, supplements, sodium, protein, fiber, fat, energy density, food form (solid/beverage); Additional model adjustments: History of stroke, angina, hypertension, diabetes, intake of coffee, fruit, vegetables, processed meat, and fish; Limitations:; - Not all key confounders accounted for; - No information on non-completers; - Exposure data collection tool not validated; - Exposure data only measured at baseline; - No preregistered data analysis plan; Funding sources:; Swedish Research Council Committee for Medicine and the Swedish Research Council Committee for Infrastructure
Shah, 2018 (https://www.amjmed.com/article/S0002-9343(17)30840-9/fulltext) ^21^; Prospective Cohort Study, Cooper Center Longitudinal Study, United States; Analytic N=11376; Power: NR; Recruitment: patients at the Cooper Clinic medical practice in Dallas, TX (‘provides patients an individualized, in-depth picture of their health, an action plan to improve it and their test results in <1 day’); Participant characteristics: adults; - Sex (female): 25%; - Age: ~47y; - Race/ethnicity: Predominantly non-Hispanic white; - SES: NR; - Anthropometrics: BMI: 25.8 kg/m^2^; - Physical activity: MET-h/wk ~17.6; - Smoking: Current: 12%; Summary of findings:; In a sample of generally healthy US adults, added sugars intake (examined as a component of the DASH Diet) was not associated with risk of CVD mortality over a follow-up period of ~18y. | Exposure of interest: Added sugar (as a component of the DASH Diet); Comparators: Quintiles of AS intake; [underlined: Exposure assessment method and timing]:; - 3-d diet record; - At baseline (1987-1999); Added sugars intake:; - <3.5%: 1590; - 3.5-9.1%: 4782; - >9.1%: 3892; Outcome assessment methods/timing:; - Follow up avg: 18y; - Health outcomes measured: CVD Mortality; - Mortality assessed via National Death Index; CVD deaths identified using International Classification of Diseases; - Occurrences: 249 | [underlined: CVD Mortality], Cox proportional hazard regression, HR (95% CI); Added sugars: NS | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, alcohol intake, physical activity, smoking; - Other factors considered: total energy intake, anthropometry; Confounders NOT accounted for:; - Key confounders: race/ethnicity, SES, naturally occurring sugar intake; - Other factors considered: menopausal status, medications, supplements, sodium, protein, fiber, fat, energy density, family history of CVD, food form (solid/beverage); Additional model adjustments: LDL, SBP, glucose, intake of fruit, vegetable, nuts/legumes, dairy, whole grain, sodium, & red/processed meats; Limitations:; - Not all key confounders accounted for; - Exposure data only measured once; - No information on non-completers; - No preregistered data analysis plan; Funding sources:; None
Sonestedt, 2015 (https://pubmed.ncbi.nlm.nih.gov/25898210-the-association-between-carbohydrate-rich-foods-and-risk-of-cardiovascular-disease-is-not-modified-by-genetic-susceptibility-to-dyslipidemia-as-determined-by-80-validated-variants/) ^22^; Prospective Cohort Study, Malmö Diet and Cancer Study (MDCS), Sweden; Analytic N=26445; Power: NR; Recruitment: all men and women born between 1923 and 1945 (men) or 1950 (women) and living in Malmö were invited to participate (personal letters and ads in newspapers and public areas); Participant characteristics: adults; - Sex (female): 62%; - Age: ~60y; - Race/ethnicity: NR; - SES: NR; - Anthropometrics: BMI ~26 kg/m^2^; - Physical activity: NR; - Smoking: NR; Summary of findings:; In a group of Swedish adults, added sugars intake broken down into three food/beverage categories was not related to risk of ischemic CVD events. | Exposure of interest: Sucrose (% TEI), Cookies and cakes (g/d), sugar and sweets (g/d), SSBs (g/d); Comparators: Quintiles of intake; Q1 = REF OR Tertiles if >25% of participants were non-consumers (SSBs); [underlined: Exposure assessment method and timing]:; - Diet history questionnaire, validated; - At baseline (1991-‘96) only; Study added sugars intake: NR; Outcome assessment methods/timing:; - Avg follow up ~14y; - Health outcomes measured: Incident ischemic CVD (iCVD) event (i.e., coronary events and ischemic stroke); - Data identified through linkage to the Swedish Hospital Discharge Registry, Cause-of-death Registry, and local stroke registry (STROMA) | [underlined: Incident iCVD event], Cox proportional hazard regression, HR (95% CI); Sucrose (% of TEI):; Q1 = REF; Q2-Q5: NS; P-trend = 0.18; Cookies & Cakes (g/d):; Q1 = REF; Q2-Q5: NS; P-trend = 0.15; Sugar & Sweets (g/d):; Q1 = REF; Q2-Q5: NS; P-trend = 0.46; SSBs (g/d):; T1 = REF; T2-T3: NS; P-trend = 0.69; Excluding participants who reported past dietary changes did not affect results; Excluding BMI from the model did not affect results | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, race/ethnicity, SES, alcohol intake, physical activity, anthropometry, smoking; - Other factors considered: total energy intake, anthropometry; Confounders NOT accounted for:; - Key confounders: race/ethnicity, naturally occurring sugar intake; - Other factors considered: menopausal status, medications, supplements, sodium, protein, fiber, fat, energy density, family history of CVD, food form (solid/beverage); Additional model adjustments: Season of data collection, diet method version; Limitations:; - Not all key confounders accounted for; - No information on non-completers; - Exposure data only measured at baseline; - No preregistered data analysis plan; Funding sources:; Swedish Medical Research Council; Swedish Society for Medical Research; Swedish Heart and Lung Foundation; Skåne University Hospital; Albert Påhlsson Research Foundation; Crafoord Foundation
Warfa, 2016 (https://pubmed.ncbi.nlm.nih.gov/27774913-association-between-sucrose-intake-and-acute-coronary-event-risk-and-effect-modification-by-lifestyle-factors-malmo-diet-and-cancer-cohort-study/) ^23^; Prospective Cohort Study, Malmö Diet and Cancer Study (MDCS), Sweden; Baseline N=28098, Analytic N=26190; Attrition: NR; Power: NR; Recruitment: research invitations in public areas or personal letter sent to population; Participant characteristics: adults with no history of CVD or diabetes; - Sex (female): 62%; - Age: 58y (44-73y); - Race/ethnicity: NR; - SES: Education elementary or less: ~42%; - Anthropometrics: BMI: ~25.5 kg/m^2^; - Physical activity: Lowest: 23%; - Smoking: Current: 32%; Summary of findings:; In a sample of Swedish adults, elevated risk of coronary events was observed in participants consuming >15% of their total, non-alcohol energy intake from sucrose. This relationship remained when the reference group was the lowest level of sucrose intake (<5%) and the mid-level of intake (7.5-10%). | Exposure of interest: Total sucrose intake as a percentage of non-alcohol energy intake; calculated for all foods and beverages included in the Swedish Food Database (food groups: sweets, chocolates, sugar and jam, fruit juice, SSBs, cakes and pastries); Comparators: AS as percentage of total, non-alcohol energy intake; - <5%; - 5-7.5%; - 7.5-10%; - 10-15%; - >15%; [underlined: Exposure assessment method and timing]:; - 7-d food diary; - Semi-quantitative FFQ; - Diet history interview; - At baseline only; Outcome assessment methods/timing:; - Assessed from recruitment (1991-’96) until end of follow-up (2013) (avg follow up: 17y); - Health outcomes measured: coronary events, defined as a fatal or non-fatal MI or death attributable to ischaemic heart disease; - Data obtained from Swedish Hospital Discharge Register and the Cause of Death Register | [underlined: Incident coronary events (n=2493)], Cox proportional hazards regression, HR (95% CI); Categories of sucrose intake by % TEI:; <5%: REF; 5-7.5%: 0.97 (0.85, 1.11); 7.5-10%: 1.02 (0.89, 1.16); 10-15%: 1.00 (0.87, 1.15); >15%: 1.34 (1.11, 1.63); P for trend: 0.01; Categories of sucrose intake by % TEI (adjusted for waist circumference):; <5%: REF; 5-7.5%: 0.99 (0.87, 1.13); 7.5-10%: 1.03 (0.90, 1.18); 10-15%: 1.02 (0.89, 1.18); >15%: 1.37 (1.13, 1.66); P for trend: 0.008; Middle group as reference (adjusted for waist circumference):; <5%: 0.97 (0.85, 1.11); 5-7.5%: 0.96 (0.86, 1.07); 7.5-10%: REF; 10-15%: 0.99 (0.89, 1.11); >15%: 1.33 (1.12, 1.58); [Data are also available in the paper that:; - Adjust for waist circumference; - Control for participants who are potential energy misreporters and those who reported past dietary change; - Show associations between each AS food/bev category and coronary events] | TEI adjusted: Yes; Confounders accounted for:; - Key confounders: sex, age, SES, alcohol intake, physical activity, smoking; - Other factors considered: total energy intake, anthropometry; Confounders NOT accounted for:; - Key confounders: race/ethnicity, naturally occurring sugar intake; - Other factors considered: menopausal status, medications, supplements, sodium, protein, fiber, fat, energy density, family history of CVD, food form (solid/beverage); Additional model adjustments: Method of data collection, season of data collection, intakes of fruits, vegetables, whole grains, coffee, fermented milk, meat, and fish; Limitations:; - Not all key confounders accounted for; - Exposure assessed at baseline only; - No preregistered data analysis plan; Funding sources:; Swedish Research Council; Swedish Society for Medical Research, Albert Påhlsson Foundation; Crawfoord Foundation; ALF government

Table 5 Risk of bias for randomized controlled trials examining added sugars consumption and risk of cardiovascular disease in adults^viii,^ ^ix^

| Randomization | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of the reported result
Bruun, 2015^4^ | Some Concerns | Some Concerns | Some Concerns | Low | Some Concerns
Engel, 2018^5^ | Some Concerns | Low | Low | Low | Some Concerns
Hernandez-Cordero, 2014^6^ | Some Concerns | Low | Low | Low | Some Concerns
Madero, 2015^7^ | Low | Low | Low | Low | Some Concerns
Markey, 2016,^8^ Crossover | Some Concerns | Low | Low | Low | Some Concerns
Umpleby, 2017,^9^ Crossover | Low | Low | Low | Low | Some Concerns

Table 6 Risk of bias for observational studies examining added sugars consumption and risk of cardiovascular disease in adults^x^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Barrington, 2016^10^ | Serious | Low | Moderate | Moderate | Moderate | Low | Moderate
Collin, 2019^11^ | Serious | Low | Low | Moderate | Moderate | Low | Moderate
Kulezic, 2019^12^ | Serious | Low | Low | Moderate | Low | Low | Moderate
Liu, 2018^13^ | Serious | Low | Low | Moderate | Moderate | Low | Moderate
Malik, 2019^14^ | Serious | Low | Low | Low | Low | Low | Moderate
Mullee, 2019^15^ | Serious | Low | Moderate | Moderate | Low | Low | Moderate
Nagata, 2019^16^ | Moderate | Low | Low | Moderate | Low | Low | Moderate
Odegaard, 2015^17^ | Serious | Low | Moderate | Moderate | Low | Low | Moderate
Ogilvie, 2017^18^ | Serious | Low | Moderate | Moderate | Moderate | Low | Moderate
Pase, 2017^19^ | Serious | Low | Low | Low | Moderate | Low | Moderate
Rahman, 2015^20^ | Serious | Low | Moderate | Moderate | Moderate | Low | Moderate
Shah, 2018^21^ | Serious | Low | Low | Moderate | Moderate | Low | Moderate
Sonestedt, 2015^22^ | Serious | Low | Low | Moderate | Moderate | Low | Moderate
Warfa, 2016^23^ | Serious | Low | Low | Moderate | Low | Low | Moderate

ii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iii Abbreviations: Avg: average; B: beta; BMI: body mass index; CI: confidence interval; CVD: cardiovascular disease; d: day(s); DBP: diastolic blood pressure; dL: deciliter(s); FFQ: food frequency questionnaire; f/u: follow-up; g: gram(s); HDL: high-density lipoprotein cholesterol; hr: hour; kg/m2: kilograms per meters squared; LDL: low-density lipoprotein cholesterol; mg: milligram(s); ml: milliliter(s); mo: month(s); NS: not significant; NR: not reported; RCT: randomized controlled trial; REF: reference group; SBP: systolic blood pressure; SD: standard deviation; SE: standard error; SES: socioeconomic status; svg: serving(s); TC: total cholesterol; TEI: total energy intake; TG: triglyceride; wk: week(s); y: year(s) Red font indicates a statistically significant detrimental relationship, and green font indicates a statistically significant beneficial relationship.

iv A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

v Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

vi Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

vii Abbreviations/short-hand: Avg: average; B: beta; BMI: body mass index; CI: confidence interval; CVD: cardiovascular disease; d: day(s); DBP: diastolic blood pressure; dL: deciliter(s); FFQ: food frequency questionnaire; f/u: follow-up; g: gram(s); HDL: high-density lipoprotein cholesterol; hr: hour; kg/m2: kilograms per meters squared; L: liter(s); LDL: low-density lipoprotein cholesterol; mg: milligram(s); ml: milliliter(s); mo: month(s); N/A: not applicable; NS: not significant; NR: not reported; RCT: randomized controlled trial; REF: reference group; SBP: systolic blood pressure; SD: standard deviation; SE: standard error; SES: socioeconomic status; svg: serving(s); TC: total cholesterol; TEI: total energy intake; TG: triglyceride; wk: week(s); y: year(s) Red font indicates a statistically significant detrimental relationship, and green font indicates a statistically significant beneficial relationship.

viii A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

ix Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

x Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )