# References of the articles included in the rapid review

1 Turner L, Calvert HG. The Academic, Behavioral, and Health Influence of Summer Child Nutrition Programs: A Narrative Review and Proposed Research and Policy Agenda. J Acad Nutr Diet. 2019;119(6):972–983.30979634
2 Collins AM, Klerman JA, Briefel R, . A Summer Nutrition Benefit Pilot Program and Low-income Children’s Food Security. Pediatrics. 2018;141(4).
3 Nalty CC, Sharkey JR, Dean WR. School-based nutrition programs are associated with reduced child food insecurity over time among Mexican-origin mother-child dyads in Texas Border Colonias. J Nutr. 2013;143(5):708–713.23486977
4 Briefel RR, Collins AM, Wolf A, Gordon AR, Cabili CL, Klerman JA. Nutrition impacts in a randomized trial of summer food benefits to prevent childhood hunger in U.S. schoolchildren. Journal of Hunger & Environmental Nutrition. 2018;13(3):304–321.
5 Hopkins LC, Holloman C, Melnyk B, . Participation in structured programming may prevent unhealthy weight gain during the summer in school-aged children from low-income neighbourhoods: feasibility, fidelity and preliminary efficacy findings from the Camp NERF study. Public Health Nutr. 2019;22(6):1100–1112.30604663
6 Evans EW, Bond DS, Pierre DF, Howie WC, Wing RR, Jelalian E. Promoting health and activity in the summer trial: Implementation and outcomes of a pilot study. Prev Med Rep. 2018;10:87–92.29868357
7 Hunt ET, Whitfield ML, Brazendale K, Beets MW, Weaver RG. Examining the impact of a summer learning program on children’s weight status and cardiorespiratory fitness: A natural experiment. Eval Program Plann. 2019;74:84–90.30939299