# Introduction

This document describes a rapid review conducted to answer the following question: What is the relationship between participation in a USDA-funded summer feeding program and food security, food sufficiency, diet quality, food acceptance, and weight-related outcomes; and what best practices exist in summer feeding programs? The USDA-funded summer feeding programs exist in a variety of formats, including the Summer Food Service Program (SFSP), the Seamless Summer Option (SSO), and the Summer Electronic Benefits Transfer for Children (SEBTC). The SFSP provides reimbursement to approved food provision sites in low-income areas where healthy meals and snacks are served to school-aged children. This program includes schools as well as other approved sites, such as community centers, churches, and camps.^*^ The SSO has a similar in-person food provision format but is a streamlined summer option specifically for schools participating in the National School Lunch or School Breakfast Programs, and it is governed by the rules of those feeding programs.^†^ The SEBTC involves distribution of an electronic benefit amount during the summer months to families of children eligible for free- or reduced-price meals during the school year.^‡^ All program types were under consideration for this rapid review.

The USDA’s Nutrition Evidence Systematic Review (NESR) team conducted this rapid review with support from the USDA’s Office of Policy Support (OPS). NESR specializes in conducting food- and nutrition-related systematic reviews using a rigorous, protocol-driven methodology. More information about NESR is available at the following website: NESR.usda.gov.

* Summer Food Service Program. Food and Nutrition Service, United States Department of Agriculture. Accessed August 25, 2021. https://www.fns.usda.gov/sfsp/summer-food-service-program

† Seamless Summer and Other Options for Schools. Food and Nutrition Service, United States Department of Agriculture. Accessed August 25, 2021. https://www.fns.usda.gov/sfsp/seamless-summer-and-other-options-schools

‡ Summer Electronic Benefit Transfer for Children (SEBTC). Food and Nutrition Service, United States Department of Agriculture. Updated FY 2019. Accessed August 25, 2021. https://www.fns.usda.gov/ops/summer-electronic-benefit-transfer-children-sebtc