# Conclusions

## Summary statement

Based on the evidence included in this rapid review and the findings from an existing narrative review, the following summary statement was developed:

Findings from this rapid review suggest USDA-funded summer feeding programs may benefit child food security and diet quality, and both in-person food provision and electronic benefit transfer formats appear beneficial.

Initial findings suggest multi-component interventions that include a feeding program may have a beneficial impact on summer weight gain prevention. However, further research is needed to determine the effects of USDA-funded summer feeding program participation on weight-related outcomes.

## Limitations and Research Recommendations

This rapid review highlights a need for additional research on USDA-funded summer feeding programs, particularly experimental research that can help clarify the unique impact of these programs on child health outcomes of interest, including food security, food sufficiency, diet quality, food acceptance, and weight-related outcomes. The existing evidence is limited by both the number of studies and by methodological challenges in the studies themselves. Although the study design is strong for many of the trials in this rapid review, much of the data are from multi-component interventions where the unique impact of the summer feeding program cannot be determined. Multiple studies are also limited by small sample sizes and high attrition. See Table 3 for a risk of bias assessment by study.

Future research can strengthen the evidence base by including measures that give a complete picture of these outcomes, such as overall diet quality. Examining more recent, novel approaches to summer meal provision, such as those used during the COVID-19 pandemic, will also bolster these findings and help identify the most effective strategies for moving forward in this important area.

Table 2 Evidence examining the relationship between summer feeding programs and food security, food sufficiency, diet quality, food acceptance, and weight-related outcomes^a^

Study and Population Characteristics | Intervention/Exposure, Comparator and Outcome(s) | Results^*^ | Model adjustments and Study Limitations
Briefel, 2018 (https://www.tandfonline.com/doi/full/10.1080/19320248.2017.1393366), RCT,; 2012: 10 grantees, 14 locations (Cherokee Nation, Chickasaw Nation, DE, NV, TX, WA, CT, MI, MO, OR); 2013: 4 grantees, 6 locations (Chickasaw Nation, DE, MI, OR); Spring survey N=38,833, Summer survey N=44,567; Power: In 2012, calculated as subsample size needed to estimate impact of 5% in very low food security among children at 95% confidence with 80% power. In 2013, calculated to detect a difference between the 2 benefit amounts.; Participant characteristics:; - Sex (female): NR; - Age: 5-18y; - Race/ethnicity of parent/guardian: 26% Hispanic, 23% Non-Hispanic black, 42% Non-Hispanic white; - SES: 44% food insecure, 8% very low food security; 64% SNAP, 22% WIC; 100% eligible for free/reduced-price school meals; 71% below poverty line; - Anthropometrics: NR | Intervention: $60/month EBT; Comparator:; $0/month (2012 control group); $30/month (2013 control group); Participants could choose for benefits tocome through SNAP or WIC; [underlined: Intervention duration]: Summer months (including prorated benefit for partial months); Outcome assessment methods/timing:; - Baseline (spring months while school was still in session), 2012, 2013 (data pooled from 2012 & 2013); - Method: parent/guardian interview; - Outcomes of interest: child frequency of certain food/bev consumption | [underlined: Diet quality], Weighted least squares: Difference (SE) (n range=42,406-43,357); [underlined: 2012: $60 vs. $0]; Fruit & vegetable: 0.36 (0.03); F&V w/o fried potatoes: 0.36 (0.03) Whole grains: 0.49 (0.05); Dairy: 0.22 (0.03); Drank nonfat/low-fat milk: −0.54 (0.71); Added sugars: −0.18 (0.17); Added sugars excluding cereals: −0.47 (0.15); SSB: −0.59 (0.16); [underlined: 2013: $60 vs. $30]; Fruit & vegetable: 0.20 (0.03); F&V w/o fried potatoes: 0.19 (0.03); Whole grains: 0.13 (0.06); Dairy: 0.07 (0.02); Drank nonfat/low-fat milk: 0.34 (0.55); Added sugars: 0.13 (0.18); Added sugars excluding cereals: 0.02 (0.16); SSB: 0.06 (0.18); Findings broken down by model distribution method found the SEBTC-WIC model had more favorable intake levels than the SEBTC-SNAP model (data in paper) | Confounders accounted for:; - N/A; Confounders NOT accounted for:; - Key confounders: Age, sex, race/ethnicity, SES, physical activity, baseline anthropometry, participation in other food assistance programs, language spoken at home, other household characteristics; Additional model adjustments:; - Sample design, differential survey nonresponse; Limitations:; - Participant/staff blinding not possible; - Participants loss to follow up; Funding Source(s):; FNS, USDA
Collins, 2018 (https://pubmed.ncbi.nlm.nih.gov/29592869/), RCT,; 2012: 10 grantees, 14 locations (Cherokee Nation, Chickasaw Nation, DE, NV, TX, WA, CT, MI, MO, OR); 2013: 4 grantees, 6 locations (Chickasaw Nation, DE, MI, OR); Spring survey N=41,793, Summer survey N=48,449; Power: In 2012, calculated as subsample size needed to estimate impact of 5% in very low food security among children at 95% confidence with 80% power. In 2013, calculated to detect a difference between the 2 benefit amounts; Participant characteristics:; - Sex (female): NR; - Age: 5-18y; - Race/ethnicity of parent/guardian: (roughly) 26% Hispanic, 23% Non-Hispanic black, 42% Non-Hispanic white; - SES: 43% food insecure, 7% very low food security; 65% SNAP, 25% WIC; 100% eligible for free/reduced-price school meals; 71% below poverty line; - Anthropometrics: NR; *Note: this is the same dataset used by Briefel, et al. 2018 | Intervention: $60/month EBT; Comparator:; $0/month (2012 control group); $30/month (2013 control group); Participants could choose for benefits to come through SNAP or WIC; [underlined: Intervention duration]: Summer months (including prorated benefit for partial months); Outcome assessment methods/timing:; - Baseline (spring months while school was still in session), 2012, 2013 (data pooled from 2012 & 2013); - Method: parent/guardian-completed 18-item USDA Food Security Survey (last 30 days); - Outcomes of interest: food security, child frequency of certain food/bev consumption | Weighted least squares: Difference (SE); [underlined: 2012: $60 vs. $0]; Very Low Food Security (VLFS-C):; $0 benefit: 9.1% of households; $60 benefit: 6.1% of households (p<0.01); Food Insecurity (FI-C):; $0 benefit: 43.0% of households; $60 benefit: 34.7% of households (p<0.01); [underlined: 2013: $60 vs. $30]; Very Low Food Security (VLFS-C):; $30 benefit: 6.7% of households; $60 benefit: 6.1% of households (p=0.076); Food Insecurity (FI-C):; $30 benefit: 38.3% of households; $60 benefit: 34.7% of households (p<0.01); Same nutrition/diet quality outcomes as in Briefel, 2018: sig. benefit for fruit & vegetable, whole grains, and dairy; Findings broken down by model distribution method found no significant differences in food security outcomes between the SEBTC-WIC and the SEBTC-SNAP model (data in paper) | Confounders accounted for:; - N/A; Confounders NOT accounted for:; - Key confounders: Age, sex, race/ethnicity, SES, physical activity, baseline anthropometry, participation in other food assistance programs, language spoken at home, other household characteristics; Additional model adjustments:; - Sample design, differential survey nonresponse; Limitations:; - Participant/staff blinding not possible; - Participants loss to follow up; Funding Source(s):; FNS, USDA
Evans, 2018 (https://pubmed.ncbi.nlm.nih.gov/29868357/); Uncontrolled before-and-after study (using data from RCT), RI; Baseline N=81, Analytic N=75 (Attrition: 90% intervention group; 97% control group); Power: Not powered to test for intervention effects on BMIz; Participant characteristics: Intervention group only; - Sex (female): 52%; - Age: 8.6 (1.9) y (6-12y); - Race/ethnicity: 10% Non-Hispanic white; 12% Non-Hispanic black; 39% Non-Hispanic other; 39% Hispanic; - SES: 100% eligible for free/reduced-price school meals; - Anthropometrics: 45% overweight/obese | Intervention (n=51): 8-wk multi-component weight gain prevention intervention; SFSP sponsoring elementary school open sites; - 9am-1pm weekdays, ~3hr physical activity, SFSP lunch; Control group (n=30): Similar access to SFSP, no access to intervention programming; [underlined: Intervention compliance]: Attendance 66±10% of days; Outcome assessment methods/timing:; - Time point(s) of assessment: baseline, post-intervention (~3 mo later); - Outcomes: BMIz; - Method: Weight and height measured using standard procedures | These data are from the intervention group only since no within-person data were presented for the control group; [underlined: Mean change in BMIz by attendance rate:]; 1-20 days (n=13): 0.08; 21-30 days (n=20): −0.05; 31-39 days (n=13): −0.16 | Confounders accounted for:; - N/A; Confounders NOT accounted for:; - Key confounders: Age, sex, race/ethnicity, SES, physical activity, baseline anthropometry, participation in other food assistance programs, language spoken at home, other household characteristics; Additional model adjustments:; Limitations:; - Periodic low attendance; - Missing data may have differentially impacted groups; Funding Source(s):; Hassenfeld Childhood Health Innovation Institute at Brown University; National Institute of Diabetes and Digestive and Kidney Diseases (K01DK110142, EWE); USDA (SFSP portion)
Hopkins, 2018 (https://pubmed.ncbi.nlm.nih.gov/30604663/); Uncontrolled before-and-after study (using data from an RCT), Franklin County, Columbus, OH; Baseline N=87, Analytic N=81 (Attrition: 7%); Power: 20 participants/site provided 70% power to detect difference of 0.5 BMIz change between intervention and control groups at 95% confidence; Participant characteristics:; - Sex (female): 57%; - Age: 7.6 (SE=0.2) y (K-5^th^ grade); - Race/ethnicity: 90% black; 10% non-black; - SES: 59% ‘low income’ based on national poverty guidelines; - Anthropometrics: 17% overweight; 13% with obesity | Intervention:; 8-wk, 3-arm, multicomponent weight gain prevention summer camp; - Standard Care (nutrition & PA); - Enhanced Care (nutrition, PA, mental health); Comparator:; - Active Control (4-H programming—non nutrition-, PA-, or mental health-related); All participants had access to SFSP; [underlined: Intervention compliance]: attendance reported by group in paper; Outcome assessment methods/timing:; - Baseline and post-intervention; - Outcomes: BMIz, diet quality, food acceptance; - Method: 24hr dietary recalls (parent-assisted for younger children) administered by study staff; height and weight measured by study staff using the NHANES protocol | [underlined: Weight-related outcomes] (analysis method); BMI Z-score: no sig. intervention effect; [underlined: Food acceptance], Mean change (SE) [underlined: Liked fruit]; [underlined: Standard care: −1.57 (0.41)] [underlined: Liked vegetable & fruit]; [underlined: Standard care: −3.08 (0.77)]; [underlined: Enhanced care: −0.88 (1.16)] [underlined: Healthy Snack Preference]; [underlined: Standard care: 0.77 (0.30)]; [underlined: Enhanced care: 0.67 (0.32)]; There were no other sig. intervention effects on veg, fruit, healthy snack acceptance; [underlined: Diet quality]; There were no sig. intervention effects on veg, fruit, snacking | Confounders accounted for:; - Key confounders: Race/ethnicity, SES (income), physical activity; Confounders NOT accounted for:; - Key confounders: Sex, age, baseline anthropometry (weight loss outcome only), participation in other food assistance programs, language spoken at home; Additional model adjustments:; - N/A; Limitations:; - Missing data may have differentially impacted groups; Funding Source(s):; Aetna Foundation, The Ohio State University Office of Outreach and Engagement
Hunt, 2019 (https://europepmc.org/article/med/30939299); Uncontrolled before-and-after study, Southeastern US; Baseline N=31, Analytic N=20 (Attrition: 35%); Power: NR; Participant characteristics (*Analytic N):; - Sex (female): 40%; - Age: 6.4 (0.6) y; - Race/ethnicity: 80% African American; - SES: Parent/Guardian Education: No High School Diploma: 5%; high School Diploma: 20%; college Degree: 60%; - Household Income: $19,999 or less: 5%; $20,000 - $39,999: 35%; $40,000 or more: 35%; - Anthropometrics: BMI: BMI Underweight: 5%; Normal weight: 65%; Overweight/Obese: 15% | Intervention: Daily (Monday to Thursday) academic achievement program operated by a local community organization in collaboration with a local school district.; -Structured reading opportunities and lessons, lunch, enrichment (e.g. social skills), and physical activity; All children provided SFSP breakfast, lunch, and a snack, daily.; Comparator: None; [underlined: Intervention duration]: 7 weeks (with week 4 being a holiday break); [underlined: Intervention compliance]: NR; Outcome assessment methods/timing:; - Time point(s) of assessment: Height & weight: wks 1 & 7 Diet data: wks 2 & 4; - Method: Ht & wt measured by trained research assistants using standard methods and CDC growth charts to determine BMIz.; - Diet data: Beverage and Snack Questionnaire (BSQ) completed by the participants’ parents, represents last 7 days | [underlined: Weight-related outcomes]; Median regression, median change (95% CI); - BMI: −0.2, 95% CI: (−0.9 1.4); - zBMI: 0.0, 95% CI: (−0.3 0.4); - BMI Percentile: 0.0, 95% CI: (−0.2 0.4) | Confounders accounted for:; - Key confounders: Sex; Confounders NOT accounted for:; - Key confounders: Age, race/ethnicity, SES, physical activity, baseline anthropometry, participation in other food assistance programs, language spoken at home, other household characteristics; Additional model adjustments:; - Attendance; Limitations:; - Small sample limits generalizability; - No control group; - Time period does not capture the entire typical summer break; - Many key confounders not controlled for; - High attrition; - No pre-registered protocol or data analysis plan; Funding Source(s):; - None
Nalty, 2013 (https://pubmed.ncbi.nlm.nih.gov/23486977/); PCS, Texas-Mexico border colonias; Baseline N=50, Analytic N=48 (Attrition: 4%); Power: NR; Participant characteristics:; - Sex (female): 58%; - Age: 8.5 (1.4)y (6-11y); - Race/ethnicity of mother: 100% Hispanic or Mexican; - SES: Parent report: 4% very low food security, 54% low food security; 25% marginal food security;; Child report: 10% very low food security; 52% low food security, 21% marginal food security; ≤$699 monthly income: 8.3%; - Anthropometrics: NR | Exposure of Interest: SFSP participation; Comparator: No SFSP participation; [underlined: Exposure assessment method and timing:]; Data collected through promotora researcher–administered surveys in participants’ homes. Mothers reported participation in nutrition assistance programs; Outcome assessment methods/timing:; - Time point(s) of assessment: summer (baseline), following spring (follow up); - Method: child completed Food Security Survey Module for Youth (9-item); parent completed US Children’s Food Security Scale (8-item) | [underlined: Food security]; Logistic regression, OR (95% CI) SFSP: 0.90 (0.23, 3.54); Child report: Food security was more prevalent in summer than during school year (p=0.02); Parent report: Food security did not vary between summer and school year (p=0.46) | Confounders accounted for:; - Key confounders: Race/ethnicity, SES (household income; education; marital status), participation in other food assistance programs, household size; Confounders NOT accounted for:; - Key confounders: Sex, age, physical activity; Additional model adjustments:; - Nativity: Mexico, Mothers’ group relative to children; Limitations:; - Low participant generalizability due to living conditions; - Small sample size also limits generalizability; Funding Source(s):; Robert Wood Johnson Foundation, NIH, CDC, USDA

* Bold, shaded font indicates results are statistically significant at p<0.05—green shading indicates a beneficial association; red shading indicates a detrimental relationship.

a Abbreviations: BMI: Body mass index (kg/m^2^); CDC: Centers for Disease Control and Prevention; CI: Confidence interval; NIH: National Institutes of Health; N/A: Not applicable; NR: Not reported; OR: Odds ratio; PCS: Prospective cohort study; RCT: Randomized controlled trial; SEBTC: Summer Electronic Benefit Transfer for Children; SES: Socioeconomic status; SFSP: Summer Food Service Program; SNAP: Supplemental Nutrition Assistance Program; SSO: Seamless Summer Option; USDA: United States Department of Agriculture; WIC: Nutrition Program for Women, Infants, and Children

Table 3 Risk of bias for studies examining USDA-funded summer feeding programs and food security, food sufficiency, diet quality, food acceptance, and weight-related outcomes

| Randomization | Confounding | Selection of participants | Classification of interventions | Classification of exposures | Deviations from intended interventions | Deviations from intended exposures | Missing outcome data | Outcome measurement | Selection of the reported result
Briefel, 2018, RCT * | Low | N/A | N/A | N/A | N/A | Low | N/A | Some concerns | Some concerns | Low
Collins, 2018, RCT | Low | N/A | N/A | N/A | N/A | Low | N/A | Low | Some concerns | Low
Evans, 2018, Uncontrolled before/after ^†^ | N/A | Serious | Low | Low | N/A | Moderate | N/A | Moderate | Low | Moderate
Hopkins, 2018, Uncontrolled before/after | N/A | Serious | Low | Low | N/A | Moderate | N/A | Low | Low | Low
Hunt, 2018, Uncontrolled before/after | N/A | Serious | Low | Low | N/A | Low | N/A | Moderate | Low | Moderate
Nalty, 2013, PCS ^‡^ | N/A | Serious | Low | N/A | Low | Some concerns | No information | Moderate | Moderate | Moderate

* Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (https://www.riskofbias.info/welcome/rob-2-0-tool) (RoB 2.0) (August 2019 version)”

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool” (https://www.riskofbias.info/welcome/home/current-version-of-robins-i)

‡ Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs)