# Results

## Literature search and screening results

The literature search yielded 1,845 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 1,528 titles, 235 abstracts, and 76 full-texts articles. Reasons for full-text exclusion are in Appendix 3. The body of evidence included 6 articles.

Figure 2 Literature search and screen flowchart

The literature search yielded 1,845 search results after the removal of duplicates. Dual-screening resulted in the exclusion of 1,528 titles, 235 abstracts, and 76 full-texts articles. Reasons for full-text exclusion are in Appendix 3. The body of evidence included 6 articles.

## Evidence description and synthesis

The existing narrative review by Turner and Calvert^1^ provided a thorough summary of federally funded summer feeding programs, including their characteristics, practices, and reach; the nutrition standards of the summer meals; and the impact on food insecurity, dietary patterns, weight, and academic, behavioral, and cognitive outcomes. They searched four databases, using specific keywords to identify relevant evidence. Literature from peer-reviewed publications, as well as governmental and non-governmental organization (NGO) reports were considered. The existing review^1^ covered the different summer feeding program formats, including the SFSP, the SSO, and the SEBTC. The body of evidence was small (8 peer-reviewed papers and 10 government or NGO sponsored reports) but tended to find beneficial impacts of program participation. Further details on outcome-specific findings are provided below.

Evidence from this rapid review supports the findings published in the Turner and Calvert review. Results from six articles not included in Turner and Calvert^1^ examine the relationship between USDA-funded summer feeding programs and food security, diet quality, food acceptance, and weight-related outcomes. This body of evidence includes four randomized controlled trials (RCTs) (two of which analyze the same dataset; the other two of which are treated as uncontrolled before-and after studies), one uncontrolled before-and-after study, and one prospective cohort study (PCS). See Table 2 for additional information on each study. There was no evidence available to evaluate the impact of summer feeding programs on food sufficiency or to draw conclusions around best practices, which were also outcomes of interest.

### Food security

Turner and Calvert^1^ reported a link between greater availability and accessibility of SFSP/SSO feeding programs and increased prevalence of food security. Programs that placed SFSP meal sites in locations with other summer activities for children, such as libraries, were positively perceived by recipients. Multiple studies on the SEBTC program, which provides a summer feeding option for families with limited access to in-person meal sites, also demonstrated a beneficial impact on food security.

Evidence on food security published since the Turner and Calvert review supports the conclusions drawn therein. Data from an RCT by Collins et al^2^ show significant decreases in rates of very low food security among children (defined as reduction of food intake and disruption of normal eating patterns in a child due to lack of food) and rates of food insecurity in families of school-aged children receiving monthly SEBTC benefit of $60-per-eligible-child compared to $0. A $30 monthly benefit showed mixed results when compared to the full $60 monthly benefit amount; food insecurity rates were significantly lower in the $60 group compared to the $30 group, but both $60 and $30 had a similarly beneficial impact on rates of very low food security.

A prospective cohort study by Nalty et al^3^ examined the impact of the SFSP in 6-11 year-old children in a group of small, recent immigrant towns, or colonias, on the Texas-Mexico border and found SFSP participation did not predict food security the following spring. These findings suggest school year feeding programs may have a greater long-term impact on food security, but the relationship between SFSP participation and summertime food security was not clearly evaluated in this study. The living conditions of participants in this study, which included a lack of running water, poor sanitation, and unpaved roads, limited generalizability; and this paper was not included in the existing review.^1^

Overall, the findings to date support a beneficial impact of federally funded summer feeding programs, both in-person and through electronic transfers, on food security.

### Diet quality

Turner and Calvert^1^ detailed evidence on the impact of federally funded summer feeding programs on child diet quality, specifically intake of certain food groups. Though there were no data on overall diet quality or dietary patterns, available RCT evidence suggested summer feeding program participation increased child consumption of fruits, vegetables, whole grains, and dairy, while decreasing overall consumption of added sugars, particularly from sugar-sweetened beverages (SSB).

Recent evidence parallels these findings. Briefel et al^4^ conducted an RCT in school-aged children that found a $60 SEBTC benefit increased child intake of fruits, vegetables, whole grains, and dairy, and reduced intake of added sugars (excluding cereal) and SSB, compared to no benefit. The $60 benefit also produced greater child intake of fruits, vegetables, whole grains, and dairy compared to a $30 benefit, though there was no significant difference in added sugars or SSB intake.

Hopkins et al^5^ randomized Kindergarten-5^th^ grade children to one of three multi-component groups, all of which included equal SFSP access. The three arms consisted of Active Control (non-nutrition, non-physical activity, non-mental health 4-H programming), Standard Care (nutrition and physical activity programming), and Enhanced Care (nutrition, physical activity, and mental health programming) groups. Between-group comparisons are not informative for this review since all participants had equal access to the SFSP; within-group comparisons are therefore treated as uncontrolled before-and-after data. Within-group comparisons show no significant effects on child dietary intake, specifically intake of fruits, vegetables, and SSB, from pre- to post-intervention.

In summary, the existing evidence suggests summer feeding programs may improve child intake of certain food groups. More research is needed to determine the magnitude and practical significance of these findings. In addition, more research is needed to examine the impacts of summer feeding programs on overall diet quality and/or dietary patterns.

### Weight-related outcomes

Turner and Calvert^1^ identified multiple articles that included a summer feeding component and examined weight-related outcomes, but only one that was clearly a federally funded program. That intervention study found a multi-component, education-based day camp, that included a SFSP component, decreased BMI for participants. However, the unique impact of the meal provision cannot be disentangled from the other intervention components.

Three studies identified by this rapid review examined the relationship between federally funded summer feeding programs and weight-related outcomes. All three included SFSP access as one of multiple intervention components. Therefore, the unique impact of in-person meal provision could not be determined from these studies; however, they provided evidence on the types of settings and joint activities that could bolster the impact of summer feeding programs on weight-related outcomes.

Evans et al^6^ enrolled 6-12 year-old participants in an 8-week multi-component weight gain prevention program, which focused on increasing physical activity during half-day periods in which the SFSP provided the lunch meal. Within-group data were presented for the intervention group only; therefore, the study design is treated as an uncontrolled before-and-after and evaluated as such. Participants in the intervention group showed a significant decrease in BMI z-scores over the duration of the study. This effect was moderated by attendance, such that participants who attended roughly 80% of study days (>30 of 39 days) showed a significant improvement in BMI, while those who attended less frequently did not.

Hopkins et al^5^ randomized Kindergarten-5^th^ grade participants to one of three multi-component intervention groups aimed at weight gain prevention, all of which included equal SFSP access, and found no significant change in BMI within groups across eight weeks.

Hunt et al^7^ utilized an uncontrolled before-and-after study design to assess the impact of a 7-week, multi-component summer learning program in 2^nd^ and 3^rd^ graders, which included an educational component; a SFSP breakfast, lunch, and snack; and physical activity time. They found it did not produce a significant change in BMI, BMI z-scores, or BMI percentile over seven weeks.

These findings suggest federally funded summer feeding programs may have a beneficial impact on weight-related outcomes, particularly summer weight gain prevention, but the findings are too mixed to draw definitive conclusions. There is a need for further research—particularly research focused on summer feeding program participation, exclusively—to determine the true impact on weight-related outcomes.

### Food acceptance

No evidence was identified, in either the existing review^1^ or the updated literature search, that directly assessed acceptance of the foods provided in these summer feeding programs; nor are there findings on the direct impact of a summer feeding program on general food acceptance.

However, indirect data from the multi-component trial by Hopkins and colleagues reported general food acceptance before and after the 8-week, 3-armed multi-component intervention described earlier.^5^ Participants in all three groups had equal access to the SFSP. Within-group differences in food acceptance were found, though not for all groups. The Standard Care group participants reported a decreased liking for vegetables and fruit at eight weeks compared to baseline; they conversely reported an increased preference for healthy snacks at eight weeks. The Enhanced Care group also reported increased preference for healthy snacks. Although these findings cannot detect the impact of the SFSP on food acceptance, they do identify components of summer programs that could be combined with the SFSP to impact preferences and behaviors.