# Methods

This rapid review was informed by an existing narrative review by Turner and Calvert^1^ on the same topic. Given how recently the existing review^1^ was published, the goal of this rapid review was to confirm the completeness of their literature search, identify relevant evidence published since their search ended in April 2018, and determine how the new literature aligns with the conclusions made by Turner and Calvert.^1^

## Develop a protocol

The analytic framework for the rapid review examining the relationship between USDA-funded summer feeding programs and food security, food sufficiency, diet quality, food acceptance, and weight-related outcomes is presented in Figure 1. An analytic framework visually represents the overall scope of the rapid review question and depicts the contributing elements that were examined and evaluated. The intervention or exposure of interest is USDA-funded summer feeding programs, including all types of models (e.g., SFSP, SSO, and SEBTC), and USDA-funded multi-component summer programs including a food provision component in school-aged children and adolescents. The comparators are different types of summer feeding programs, including non-USDA funded programs, and no participation in a summer feeding program. The outcomes are food security, food sufficiency, diet quality, food acceptance, and weight-related outcomes in school-aged children and adolescents, as well as any identifiable best practices across different program types. The key confounders are sex, age, race/ethnicity, socioeconomic status (SES), physical activity, baseline anthropometry (weight loss outcome only), participation in other food assistance programs, language spoken at home, and other household characteristics (e.g., age distribution of children, household size, household member with difficulty in daily activity). The confounders may impact the relationships of interest.

Figure 1 Analytic Framework

An analytic framework visually represents the overall scope of the rapid review question and depicts the contributing elements that were examined and evaluated. The intervention or exposure of interest is USDA-funded summer feeding programs, including all types of models (e.g., SFSP, SSO, and SEBTC), and USDA-funded multi-component summer programs including a food provision component in school-aged children and adolescents. The comparators are different types of summer feeding programs, including non-USDA funded programs, and no participation in a summer feeding program. The outcomes are food security, food sufficiency, diet quality, food acceptance, and weight-related outcomes in school-aged children and adolescents, as well as any identifiable best practices across different program types. The key confounders are sex, age, race/ethnicity, socioeconomic status (SES), physical activity, baseline anthropometry (weight loss outcome only), participation in other food assistance programs, language spoken at home, and other household characteristics (e.g., age distribution of children, household size, household member with difficulty in daily activity). The confounders may impact the relationships of interest.

## Search for and select studies

The inclusion and exclusion criteria for the rapid review examining the effect of USDA-funded summer feeding programs on food security, food sufficiency, diet quality, food acceptance, and weight-related outcomes are presented in Table 1. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search will be included in or excluded from the rapid review.

Initial, informal evidence scanning identified an existing narrative review on the same topic covering literature published between January 2000 and April 2018^1^; therefore, the team decided to verify all relevant literature was captured by the existing review,^1^ as well as to capture literature published since April 2018. The NESR librarian developed and NESR analysts reviewed a comprehensive search strategy to identify relevant articles published between January 2000 and August 2020 that address the rapid review question. The search strategy was implemented in 3 databases: PubMed, Embase, and Education Resources Information Center (ERIC). The full search strategies are described in Appendix 2.

Two NESR analysts then independently screened all search results. Analysts compared the list of articles included during screening with the reference list from the existing narrative review, and those either not included in or published since the existing review^1^ were included in this rapid review.

Table 1 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Uncontrolled trials | - Case-control studies; - Nested case-control studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - USDA-funded summer feeding programs (e.g., Summer Food Service Program (SFSP), Seamless Summer Option (SSO), SEBTC (electronic benefits)); - Multi-component summer programs including a USDA-funded feeding component | - Feeding program during the school year
Comparator | - Different type of summer feeding program, including non-USDA funded programs, varying in characteristics such as mode of delivery or duration; - No participation in a summer feeding program
Outcomes | - Food security; - Food sufficiency; - Diet quality; - Food acceptance; - Weight-related outcomes:; ○ Weight, weight-for-age; ○ Body mass index (BMI), BMI z-score; ○ Body composition (e.g., % fat mass, % fat-free mass); ○ Incidence and prevalence of underweight, healthy weight, overweight, obesity | - Any other outcomes
Publication date | - January 2000 – August 2020 | - Before January 2000
Publication status | - Articles that have been peer-reviewed; - Grey literature: reports that have not been peer-reviewed but are available from government, research, and nonprofit organizations (e.g., USDA, state-level reports, Feeding America, FRAC, No Kid Hungry) | - Articles that represent incomplete work, including unpublished manuscripts, abstracts, and conference proceedings
Language | - Articles published in English | - Articles published in languages other than English
Country^*^ | - Studies conducted in the United States | - Studies conducted outside the United States
Study participants | - Human participants; ○ Males; ○ Females | - Non-human participants (e.g., animal studies, in-vitro models)
Age of study participants | - Age at intervention, exposure, outcome:; ○ Children and adolescents (5-18 years) | - Age at intervention, exposure, or outcome:; ○ Infants, toddlers, and young children (birth to 4y); ○ Adults (19-64 years); ○ Older adults (65 years and older)

## Extract data and assess the risk of bias

One NESR analyst extracted data from each study, and a second analyst verified all data. One NESR analyst completed a risk of bias assessment for each study, and a second analyst verified their responses.

## Synthesize the evidence and develop a summary statement

The findings of any newly published articles identified in the literature search were summarized in the context of conclusions drawn in the existing review.^1^ Analysts noted areas of agreement and disagreement between the two reviews.

## Identify limitations and recommend future research

The synthesis process identified key limitations in the existing body of evidence, as well as areas of future research that could bolster findings in this area.

* In order to determine the inclusion exclusion criteria for country, the Human Development classification was used. This classification is based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead ( The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups )