# Acknowledgments and funding

NESR staff: developed the protocol for examining the scientific evidence, including the inclusion and exclusion criteria; reviewed all studies that met the set criteria; discussed the body of evidence for each question; and wrote the summary statements.

NESR staff worked with the review sponsors, the OPS SNRAD team, to determine the scope of the question and develop the rapid review protocol.

- Chanchalat Chanhatasilpa, PhD
- Holly Figueroa, MSW
- Conor McGovern, MA
- Kelley Scanlon, PhD, RD