# Appendix 3 Excluded articles

The following table lists the articles excluded after full-text screening for this rapid review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

| Citation | Rationale
1 | (2003). Summer snacking. CDS Rev, 96(3), 34. doi:#electronic resource number#. | Publication Status
2 | (2011). Cooperation in USDA studies and evaluations, and full use of federal funds in nutrition assistance programs nondiscretionary provisions of the Healthy, Hunger-Free Kids Act of 2010, Public Law 111-296. Final Rule. Fed Regist, 76(125), 37979-83. doi:#electronic resource number#. | Study Design; Publication Status; Other
3 | Barnidge, EK, Chapnick, M, Sawicki, M, Baker, EA, Huang, J. Food Insecurity in the Summer: A Rural–Urban Comparison of African American Households With Children. Journal of Hunger and Environmental Nutrition. 2017. 12:221-236. doi:10.1080/19320248.2016.1255581. | Outcome
4 | Bleiweiss-Sande, R.,Sacheck, J. M.,Chui, K.,Goldberg, J. P.,Bailey, C.,Evans, E. W. (2020). Processed food consumption is associated with diet quality, but not weight status, in a sample of low-income and ethnically diverse elementary school children. Appetite, 151(#issue#), 104696. doi:10.1016/j.appet.2020.104696. | Intervention/Exposure; Comparator
5 | Bohnert, A. M.,Bates, C. R.,Heard, A. M.,Burdette, K. A.,Ward, A. K.,Silton, R. L.,Dugas, L. R. (2017). Improving Urban Minority Girls’ Health Via Community Summer Programming. J Racial Ethn Health Disparities, 4(6), 1237-1245. doi:10.1007/s40615-016-0333-x. | Intervention/Exposure
6 | Brazendale, K.,Beets, M. W.,Turner-McGrievy, G. M.,Kaczynski, A. T.,Pate, R. R.,Weaver, R. G. (2018). Children’s Obesogenic Behaviors During Summer Versus School: A Within-Person Comparison. J Sch Health, 88(12), 886-892. doi:10.1111/josh.12699. | Intervention/Exposure
7 | Brown, C. W.,Alexander, D. S.,Warren, C. A.,Anderson-Booker, M. (2017). A Qualitative Approach: Evaluating the Childhood Health and Obesity Initiative Communities Empowered for Success (CHOICES) Pilot Study. J Racial Ethn Health Disparities, 4(4), 549-557. doi:10.1007/s40615-016-0257-5. | Intervention/Exposure
8 | Bruce, J. S.,De La Cruz, M. M.,Lundberg, K.,Vesom, N.,Aguayo, J.,Merrell, S. B. (2019). Combating Child Summer Food Insecurity: Examination of a Community-Based Mobile Meal Program. J Community Health, 44(5), 1009-1018. doi:10.1007/s10900-019-00675-0. | Outcome
9 | Bruce, J. S.,De La Cruz, M. M.,Moreno, G.,Chamberlain, L. J. (2017). Lunch at the library: examination of a community-based approach to addressing summer food insecurity. Public Health Nutr, 20(9), 1640-1649. doi:10.1017/s1368980017000258. | Population
10 | Carpenter, L. R.,Smith, T. M.,Stern, K.,Boyd, L. W.,Rasmussen, C. G.,Schaffer, K.,Shuell, J.,Broussard, K.,Yaroch, A. L. (2017). Meals for Good: An innovative community project to provide healthy meals to children in early care and education programs through food bank catering. Prev Med Rep, 8(#issue#), 210-214. doi:10.1016/j.pmedr.2017.10.015. | Intervention/Exposure; Outcome; Population
11 | Cobern, J. A.,Shell, K. J.,Henderson, E. R.,Beech, B. M.,Batlivala, S. P. (2015). The Summer Food Service Program and the Ongoing Hunger Crisis in Mississippi. J Miss State Med Assoc, 56(10), 300-2. doi:#electronic resource number#. | Study Design
12 | Collins, AM, Klerman, JA. Improving Nutrition by Increasing Supplemental Nutrition Assistance Program Benefits. Am J Prev Med. 2017. 52:S179-s185. doi:10.1016/j.amepre.2016.08.032. | Included in Turner 2019 review
13 | Cotwright, C. J.,Alvis, C.,de Jesus Jimenez, F.,Farmer, P.,Okoli, C.,Delane, J.,Cox, G. O. (2020). Improving Willingness to Try Fruits and Vegetables Among Low-Income Children Through Use of Characters. Health Equity, 4(1), 84-90. doi:10.1089/heq.2019.0113. | Intervention/Exposure
14 | Cullen, D, Blauch, A, Mirth, M, Fein, J. Complete Eats: Summer Meals Offered by the Emergency Department for Food Insecurity. Pediatrics. 2019. 144:#pages#. doi:10.1542/peds.2019-0201. | Outcome
15 | De La Cruz, M. M.,Phan, K.,Bruce, J. S. (2020). More to offer than books: stakeholder perceptions of a public library-based meal programme. Public Health Nutr, 23(12), 2179-2188. doi:10.1017/s1368980019004336. | Outcome
16 | Di Noia, J.,Byrd-Bredbenner, C. (2013). Adolescent fruit and vegetable intake: influence of family support and moderation by home availability of relationships with afrocentric values and taste preferences. J Acad Nutr Diet, 113(6), 803-8. doi:10.1016/j.jand.2013.02.001. | Intervention/Exposure
17 | Di Noia, J.,Contento, I. R. (2010). Fruit and vegetable availability enables adolescent consumption that exceeds national average. Nutr Res, 30(6), 396-402. doi:10.1016/j.nutres.2010.06.008. | Intervention/Exposure
18 | Di Noia, J.,Cullen, K. W. (2015). Fruit and Vegetable Attitudes, Norms, and Intake in Low-Income Youth. Health Educ Behav, 42(6), 775-82. doi:10.1177/1090198115578752. | Intervention/Exposure; Comparator
19 | Ehrenberg, S.,Leone, L. A.,Sharpe, B.,Reardon, K.,Anzman-Frasca, S. (2019). Using repeated exposure through hands-on cooking to increase children’s preferences for fruits and vegetables. Appetite, 142(#issue#), 104347. doi:10.1016/j.appet.2019.104347. | Intervention/Exposure
20 | El Mikati, H. K.,Boateng, A. O.,McKinney, B. M.,Haberlin-Pittz, K.,Pike, J.,Perry, P.,Hannon, T. S.,Yazel-Smith, L. (2020). Forever-Fit Summer Camp: The Impact of a 6-Week Summer Healthy Lifestyle Day Camp on Anthropometric, Cardiovascular, and Physical Fitness Measures in Youth With Obesity. J Prim Care Community Health, 11(#issue#), 2150132720903888. doi:10.1177/2150132720903888. | Intervention/Exposure
21 | Gachupin, Francine C.,Morehouse, Laura,Bergier, Nicole,Thomson, Cynthia (2019). Describing a Public-Health Summer Camp for Underserved Children: Healthy 2B Me. #journal#, 90(4), 39-51. doi:#electronic resource number#. | Intervention/Exposure
22 | George, G. L.,Schneider, C.,Kaiser, L. (2016). Healthy Lifestyle Fitness Camp: A Summer Approach to Prevent Obesity in Low-Income Youth. J Nutr Educ Behav, 48(3), 208-12.e1. doi:10.1016/j.jneb.2015.12.010. | Intervention/Exposure
23 | Gordon, AR, Briefel, RR, Collins, AM, Rowe, GM, Klerman, JA. Delivering Summer Electronic Benefit Transfers for Children through the Supplemental Nutrition Assistance Program or the Special Supplemental Nutrition Program for Women, Infants, and Children: Benefit Use and Impacts on Food Security and Foods Consumed. J Acad Nutr Diet. 2017. 117:367-375.e2. doi:10.1016/j.jand.2016.11.002. | Included in Turner 2019 review
24 | Gorman, K. (2006). Kid’s summer shape-up: Encourage better snack choices and more activity. Obesity Management, 2(3), 119. doi:10.1089/obe.2006.2.119. | Intervention/Exposure; Publication Status; Other
25 | Halpern-Felsher, B.,McLaughlin, S. (2016). The Importance of Scientific Mentoring Programs for Underrepresented Youth. J Health Dispar Res Pract, 9(5), 87-89. doi:#electronic resource number#. | Intervention/Exposure; Outcome
26 | Hanson, K. L.,Kolodinsky, J.,Wang, W.,Morgan, E. H.,Pitts, S. B. J.,Ammerman, A. S.,Sitaker, M.,Seguin, R. A. (2017). Adults and Children in Low-Income Households that Participate in Cost-Offset Community Supported Agriculture Have High Fruit and Vegetable Consumption. Nutrients, 9(7), #Pages#. doi:10.3390/nu9070726. | Intervention/Exposure
27 | Hatcher, Daniel W.,FitzSimons, Crystal Weedall,Turley, Jill R. (2014). The Role of Out-of-School Time in Reducing Hunger and Preventing Obesity. #journal#, #volume#(#issue#), #Pages#. doi:#electronic resource number#. | Outcome; Publication Status; Other
28 | Heim, S.,Stang, J.,Ireland, M. (2009). A garden pilot project enhances fruit and vegetable consumption among children. J Am Diet Assoc, 109(7), 1220-6. doi:10.1016/j.jada.2009.04.009. | Intervention/Exposure
29 | Hopkins, L. C.,Fristad, M.,Goodway, J. D.,Eneli, I.,Holloman, C.,Kennel, J. A.,Melnyk, B.,Gunther, C. (2016). Camp NERF: methods of a theory-based nutrition education recreation and fitness program aimed at preventing unhealthy weight gain in underserved elementary children during summer months. BMC Public Health, 16(1), 1122. doi:10.1186/s12889-016-3765-7. | Other
30 | Hopkins, L. C.,Fristad, M.,Goodway, J. D.,Melnyk, B.,Eneli, I.,Holloman, C.,Kennel, J. A.,Webster, A.,Sharn, A. R.,Gunther, C. (2018). Feasibility and acceptability of technology-based caregiver engagement strategies delivered in a summertime childhood obesity prevention intervention: results from an internal pilot of the Camp NERF (Nutrition, Education, Recreation, and Fitness) study. Pilot Feasibility Stud, 4(#issue#), 153. doi:10.1186/s40814-018-0340-2. | Outcome
31 | Hopkins, L. C.,Gunther, C. (2015). A Historical Review of Changes in Nutrition Standards of USDA Child Meal Programs Relative to Research Findings on the Nutritional Adequacy of Program Meals and the Diet and Nutritional Health of Participants: Implications for Future Research and the Summer Food Service Program. Nutrients, 7(12), 10145-67. doi:10.3390/nu7125523. | Study Design; Outcome
32 | Hopkins, L. C.,Hooker, N. H.,Gunther, C. (2017). Securing a Stop to the Summer Setback: Policy Considerations in the Future Expansion of the Summer Electronic Benefit Transfer for Children. J Nutr Educ Behav, 49(8), 692-699.e1. doi:10.1016/j.jneb.2016.10.010. | Study Design
33 | Hopkins, L. C.,Penicka, C.,Evich, C.,Jones, B.,Gunther, C. (2018). Project SWEAT (Summer Weight and Environmental Assessment Trial): study protocol of an observational study using a multistate, prospective design that examines the weight gain trajectory among a racially and ethnically diverse convenience sample of economically disadvantaged school-age children. BMJ Open, 8(8), e021168. doi:10.1136/bmjopen-2017-021168. | Other
34 | Hopkins, L. C.,Tiba, S.,Westrick, M.,Gunther, C. (2020). The Diet Quality of a Sample of Predominantly Racial Minority Children From Low-Income Households Is Lower During the Summer vs School Year: Results From the Project Summer Weight and Environmental Assessment Trial Substudy. J Acad Nutr Diet, #volume#(#issue#), #Pages#. doi:10.1016/j.jand.2020.06.013. | Intervention/Exposure
35 | Huang, J.,Barnidge, E. (2016). Low-income Children’s participation in the National School Lunch Program and household food insufficiency. Soc Sci Med, 150(#issue#), 8-14. doi:10.1016/j.socscimed.2015.12.020. | Intervention/Exposure
36 | Huang, J.,Barnidge, E.,Kim, Y. (2015). Children Receiving Free or Reduced-Price School Lunch Have Higher Food Insufficiency Rates in Summer. J Nutr, 145(9), 2161-8. doi:10.3945/jn.115.214486. | Intervention/Exposure
37 | Huang, J.,Kim, Y.,Barnidge, E. (2016). Seasonal Difference in National School Lunch Program Participation and Its Impacts on Household Food Security. Health Soc Work, 41(4), 235-243. doi:10.1093/hsw/hlw043. | Intervention/Exposure
38 | Jones, Denise,Jones, Dennis (2020). Transcend the Summer Slump: How Summer Programs Can Attract and Retain Low-Income High School Students. #journal#, #volume#(#issue#), #Pages#. doi:#electronic resource number#. | Intervention/Exposure
39 | Kannam, A.,Wilson, N. L. W.,Chomitz, V. R.,Ladin, K. (2019). Perceived Benefits and Barriers to Free Summer Meal Participation Among Parents in New York City. J Nutr Educ Behav, 51(8), 976-984. doi:10.1016/j.jneb.2019.05.592. | Outcome
40 | Kenney, E. L.,Lee, R. M.,Brooks, C. J.,Cradock, A. L.,Gortmaker, S. L. (2017). What Do Children Eat in the Summer? A Direct Observation of Summer Day Camps That Serve Meals. J Acad Nutr Diet, 117(7), 1097-1103. doi:10.1016/j.jand.2017.01.026. | Intervention/Exposure
41 | Kilanowski, JF, Gordon, NH. Making a Difference in Migrant Summer School: Testing a Healthy Weight Intervention. Public Health Nurs. 2015. 32:421-9. doi:10.1111/phn.12175. | Included in Turner 2019 review
42 | Kozak, A. T.,Pickett, S. M.,Jarrett, N. L.,Markarian, S. A.,Lahar, K. I.,Goldstick, J. E. (2019). Project STARLIT: protocol of a longitudinal study of habitual sleep trajectories, weight gain, and obesity risk behaviors in college students. BMC Public Health, 19(1), 1720. doi:10.1186/s12889-019-7697-x. | Intervention/Exposure; Publication Status
43 | Lee, J.,Kubik, M. Y.,Fulkerson, J. A. (2019). Diet Quality and Fruit, Vegetable, and Sugar-Sweetened Beverage Consumption by Household Food Insecurity among 8- to 12-Year-Old Children during Summer Months. J Acad Nutr Diet, 119(10), 1695-1702. doi:10.1016/j.jand.2019.03.004. | Intervention/Exposure
44 | Litt, H, Polke, A, Tully, J, Volerman, A. Addressing Food Insecurity: An Evaluation of Factors Associated with Reach of a School-Based Summer Meals Program. J Acad Nutr Diet. 2020. #volume#:#pages#. doi:10.1016/j.jand.2020.04.003. | Outcome
45 | Mahoney, J. L. (2011). Adolescent summer care arrangements and risk for obesity the following school year. Journal of Adolescence, 34(4), 737-749. doi:10.1016/j.adolescence.2010.08.010. | Intervention/Exposure
46 | Maxwell, A. E.,Castillo, L.,Arce, A. A.,De Anda, T.,Martins, D.,McCarthy, W. J. (2018). Eating Veggies Is Fun! An Implementation Pilot Study in Partnership With a YMCA in South Los Angeles. Prev Chronic Dis, 15(#issue#), E132. doi:10.5888/pcd15.180150. | Intervention/Exposure
47 | Miles, R.,Wang, Y.,Johnson, S. B. (2018). Neighborhood Built and Social Environments and Change in Weight Status over the Summer in Low-Income Elementary School Children. Int J Environ Res Public Health, 15(6), #Pages#. doi:10.3390/ijerph15061124. | Intervention/Exposure
48 | Miller, DP. Accessibility of summer meals and the food insecurity of low-income households with children. Public Health Nutr. 2016. 19:2079-89. doi:10.1017/s1368980016000033. | Included in Turner 2019 review
49 | National Academies of Sciences, Engineering,Medicine,,Division of, Behavioral,Social, Sciences,Education,,Board on Children, Youth,Families,,Committee on Summertime, Experiences,Child,,Adolescent Education, Health,Safety, (2019). . Shaping Summertime Experiences: Opportunities to Promote Healthy Development and Well-Being for Children and Youth, #volume#(#issue#), #Pages#. doi:10.17226/25546. | Study Design; Outcome
50 | Oberholser, C. A.,Tuttle, C. R. (2004). Assessment of household food security among food stamp recipient families in Maryland. Am J Public Health, 94(5), 790-5. doi:10.2105/ajph.94.5.790. | Outcome; Other
51 | Olvera, N.,Leung, P.,Kellam, S. F.,Liu, J. (2013). Body fat and fitness improvements in Hispanic and African American girls. J Pediatr Psychol, 38(9), 987-96. doi:10.1093/jpepsy/jst041. | Intervention/Exposure
52 | Oo, K.,Stephenson, T.,Hege, A.,Brewer, D.,Gamboa, L.,Hildesheim, L.,Serra, L.,Houlihan, J.,Koempel, A. (2020). Addressing Childhood Hunger during the Summer Months: Using Gleaned Produce for Snacks and Interactive Nutrition Education on Food Systems and Healthy Eating. Journal of Hunger and Environmental Nutrition, #volume#(#issue#), #Pages#. doi:10.1080/19320248.2020.1744497. | Intervention/Exposure
53 | Parente, Maria E.,Sheppard, Adam,Mahoney, Joseph L. (2012). Parental Knowledge as a Mediator of the Relation between Adolescent Summer Care Arrangement Configurations and Adjustment the Following School Year. #journal#, 16(2), 84-97. doi:#electronic resource number#. | Intervention/Exposure
54 | Park, K. S.,Lee, M. G. (2015). Effects of summer school participation and psychosocial outcomes on changes in body composition and physical fitness during summer break. J Exerc Nutrition Biochem, 19(2), 81-90. doi:10.5717/jenb.2015.15052005. | Intervention/Exposure
55 | Phillips, R.,Harper, S.,Gamble, S. (2007). Summer programming in rural communities: unique challenges. New Dir Youth Dev, #volume#(114), 65-73. doi:10.1002/yd.213. | Study Design
56 | Pierce, B.,Bowden, B.,McCullagh, M.,Diehl, A.,Chissell, Z.,Rodriguez, R.,Berman, B. M.,D. Adamo CR (2017). A Summer Health Program for African-American High School Students in Baltimore, Maryland: Community Partnership for Integrative Health. Explore (NY), 13(3), 186-197. doi:10.1016/j.explore.2017.02.002. | Intervention/Exposure
57 | Reesor, L.,Moreno, J. P.,Johnston, C. A.,Hernandez, D. C. (2019). School-Based Weight Management Program Curbs Summer Weight Gain Among Low-Income Hispanic Middle School Students. J Sch Health, 89(1), 59-67. doi:10.1111/josh.12713. | Intervention/Exposure
58 | Rodriguez, A. X.,Olvera, N.,Leung, P.,O’Connor, D. P.,Smith, D. W. (2014). Association between the summer season and body fatness and aerobic fitness among Hispanic children. J Sch Health, 84(4), 233-8. doi:10.1111/josh.12141. | Intervention/Exposure
59 | Rosenkranz, R. R.,Dzewaltowski, D. A. (2009). Promoting better family meals for girls attending summer programs. J Nutr Educ Behav, 41(1), 65-7. doi:10.1016/j.jneb.2008.02.003. | Intervention/Exposure
60 | Sallis, J. F.,Conway, T. L.,Cain, K. L.,Geremia, C.,Bonilla, E.,Spoon, C. (2019). Race/ethnic variations in school-year versus summer differences in adolescent physical activity. Prev Med, 129(#issue#), 105795. doi:10.1016/j.ypmed.2019.105795. | Intervention/Exposure
61 | Schaefle, Scott (2018). The Relationship between GEAR UP Program Involvement and Latina/o Students’ Performance on High-Stakes Tests. #journal#, 17(3), 201-214. doi:#electronic resource number#. | Intervention/Exposure; Outcome
62 | Seal, N.,Seal, J. (2011). Developing healthy childhood behaviour: outcomes of a summer camp experience. Int J Nurs Pract, 17(4), 428-34. doi:10.1111/j.1440-172X.2011.01924.x. | Intervention/Exposure
63 | Sharkey, J. R.,Dean, W. R.,Nalty, C. C. (2013). Child hunger and the protective effects of Supplemental Nutrition Assistance Program (SNAP) and alternative food sources among Mexican-origin families in Texas border colonias. BMC Pediatr, 13(#issue#), 143. doi:10.1186/1471-2431-13-143. | Intervention/Exposure
64 | Staiano, A. E.,Baker, C. M.,Calvert, S. L. (2012). Dietary Digital Diaries: Documenting Adolescents’ Obesogenic Environment. Environ Behav, 44(5), 695-712. doi:10.1177/0013916511403623. | Intervention/Exposure
65 | Tanskey, L. A.,Goldberg, J. P.,Chui, K.,Must, A.,Sacheck, J. M. (2019). Accelerated Summer Weight Gain in a Low-Income, Ethnically Diverse Sample of Elementary School Children in Massachusetts. Child Obes, 15(4), 244-253. doi:10.1089/chi.2017.0228. | Intervention/Exposure
66 | Tanskey, L. A.,Goldberg, J. P.,Chui, K.,Must, A.,Wright, C. M.,Sacheck, J. M. (2019). A qualitative exploration of potential determinants of accelerated summer weight gain among school-age children: perspectives from parents. BMC Pediatr, 19(1), 438. doi:10.1186/s12887-019-1813-z. | Intervention/Exposure
67 | Tauriello, S.,Bowker, J.,Wilding, G.,Epstein, L.,Anzman-Frasca, S. (2020). Examining associative conditioning with a positive peer context as a strategy to increase children’s vegetable acceptance. Pediatr Obes, #volume#(#issue#), e12660. doi:10.1111/ijpo.12660. | Intervention/Exposure
68 | Toossi, S. (2017). Incentivizing healthy eating in children: An investigation of the “ripple” and “temporal” effects of a reward-based intervention. Appetite, 117(#issue#), 58-66. doi:10.1016/j.appet.2017.06.011. | Intervention/Exposure
69 | Turner, L, O’Reilly, N, Ralston, K, Guthrie, JF. Identifying gaps in the food security safety net: the characteristics and availability of summer nutrition programmes in California, USA. Public Health Nutr. 2019. 22:1824-1838. doi:10.1017/s1368980018004135. | Outcome
70 | Wang, Y. C.,Vine, S.,Hsiao, A.,Rundle, A.,Goldsmith, J. (2015). Weight-related behaviors when children are in school versus on summer breaks: does income matter?. J Sch Health, 85(7), 458-66. doi:10.1111/josh.12274. | Intervention/Exposure
71 | Weaver, H. N.,Jackson, K. F. (2010). Healthy Living in Two Worlds: Testing a Wellness Curriculum for Urban Native Youth. Child Adolesc Social Work J, 27(3), 231-244. doi:10.1007/s10560-010-0197-6. | Intervention/Exposure
72 | Werner, D.,Teufel, J.,Holtgrave, P. L.,Brown, S. L. (2012). Active generations: an intergenerational approach to preventing childhood obesity. J Sch Health, 82(8), 380-6. doi:10.1111/j.1746-1561.2012.00713.x. | Intervention/Exposure
73 | White, A. H.,Maroto, M. E. (2016). Summer Meal Programs Provide an Opportunity for Nutrition Education and Physical Activity. J Acad Nutr Diet, 116(6), 905-7. doi:10.1016/j.jand.2016.04.003. | Outcome; Publication Status; Other
74 | Williams, L.,Magee, A.,Kilby, C.,Maxey, K.,Skelton, J. A. (2019). A pilot summer day camp cooking curriculum to influence family meals. Pilot Feasibility Stud, 5(#issue#), 147. doi:10.1186/s40814-019-0528-0. | Intervention/Exposure
75 | Wyker, B. A.,Jordan, P.,Quigley, D. L. (2012). Evaluation of supplemental nutrition assistance program education: application of behavioral theory and survey validation. J Nutr Educ Behav, 44(4), 360-4. doi:10.1016/j.jneb.2011.11.004. | Outcome
76 | Yen, I. H.,Gregorich, S.,Cohen, A. K.,Stewart, A. (2013). A community cohort study about childhood social and economic circumstances: Racial/ethnic differences and associations with educational attainment and health of older adults. BMJ Open, 3(4), #Pages#. doi:10.1136/bmjopen-2012-002140. | Intervention/Exposure; Population