# Appendix 2 Literature search strategy

## Databases and search terms

Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: August 21, 2020

Date range searched: January 1, 2000-August 21, 2020

Results: 1,016

#1 summer*[tiab] OR holiday*[tiab]
#2 “Meals”[Mesh] OR meal*[tiab] OR breakfast*[tiab] OR break fast*[tiab] OR lunch*[tiab] OR snack*[tiab] OR dinner*[tiab] OR supper*[tiab] OR “Food Assistance”[Mesh] OR food*[tiab] OR feed*[tiab] OR nutrition service*[tiab] OR nutrition intervention*[tiab] OR nutrition program*[tiab] OR nutritional program*[tiab] OR nutrition educat*[tiab] OR nutritional intervention*[tiab] OR nutritional educat*[tiab] OR “Food Supply”[Mesh] OR “Health Status Disparities”[Mesh] OR health disparit*[tiab] OR “Poverty”[Mesh] OR poverty[tiab] OR “Socioeconomic Factors”[Mesh] OR social economic*[tiab] OR socialeconomic[tiab] OR “Hunger”[Mesh] OR hunger[tiab]
#3 “Child”[Mesh] OR child*[tiab] OR youth*[tiab] OR “Adolescent”[Mesh] OR adolescen*[tiab] OR teen*[tiab] OR preteen*[tiab] OR pre-teen*[tiab] OR pre-adolesc*[tiab] OR preadolesc*[tiab] OR boy[tiab] OR boys[tiab] OR girl[tiab] OR girls[tiab] OR schoolchild*[tiab] OR elementary school*[tiab] OR primary school*[tiab] OR secondary school*[tiab] OR middle school*[tiab] OR junior high*[tiab] OR high school*[tiab] OR juvenile*[tiab] OR pubescent[tiab] OR pre pubescent[tiab] OR prepubescent[tiab] OR kid[tiab] OR kids[tiab]
#4 (#1 AND #2 AND #3)
#5 (#1 AND #2 AND #3) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh] NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: English, from 2000 - 2020 Sort by: Publication Date

Database: Embase

Provider: Elsevier

Date(s) Searched: August 21, 2020

Date range searched: January 1, 2000-August 21, 2020

Results: 880

#1 summer*:ab,ti OR holiday*:ab,ti
#2 ‘meal’/exp OR meal*:ab,ti OR breakfast*:ab,ti OR ‘break fast*’:ab,ti OR lunch*:ab,ti OR snack*:ab,ti OR dinner*:ab,ti OR supper*:ab,ti OR ‘food assistance’/exp OR food*:ab,ti OR feed*:ab,ti OR ‘nutrition service*’:ab,ti OR ‘nutrition intervention*’:ab,ti OR ‘nutrition program*’:ab,ti OR ‘nutritional program*’:ab,ti OR ‘nutrition educat*’:ab,ti OR ‘nutritional intervention*’:ab,ti OR ‘nutritional educat*’:ab,ti OR ‘food insecurity’/exp OR ‘health disparity’/exp OR ‘health disparit*’:ab,ti OR poverty:ab,ti OR ‘socioeconomics’/exp OR ‘social economic*’:ab,ti OR socialeconomic:ab,ti OR ‘hunger’/exp OR hunger:ab,ti
#3 ‘child’/exp OR child*:ab,ti OR youth*:ab,ti OR ‘adolescent’/exp OR adolescen*:ab,ti OR teen*:ab,ti OR preteen*:ab,ti OR ‘pre teen*’:ab,ti OR ‘pre adolesc*’:ab,ti OR preadolesc*:ab,ti OR boy:ab,ti OR boys:ab,ti OR girl:ab,ti OR girls:ab,ti OR schoolchild*:ab,ti OR ‘elementary school*’:ab,ti OR ‘primary school*’:ab,ti OR ‘secondary school*’:ab,ti OR ‘middle school*’:ab,ti OR ‘junior high*’:ab,ti OR ‘high school*’:ab,ti OR juvenile*:ab,ti OR pubescent:ab,ti OR ‘pre pubescent’:ab,ti OR prepubescent:ab,ti OR kid:ab,ti OR kids:ab,ti
#4 #1 AND #2 AND #3 AND [humans]/lim AND [english]/lim AND [2000-2020]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim)

Database: Education Resources Information Center (ERIC)

Provider: Institute of Education Sciences within the United States Department of Education

Date(s) Searched: August 21, 2020

Date range searched: January 1, 2000-August 21, 2020

Results: 504

((summer* OR holiday*) AND (meal* OR breakfast* OR ‘break fast*’ OR lunch* OR snack* OR dinner* OR supper* OR food* OR feed* OR ‘nutrition service*’ OR ‘nutrition intervention*’ OR ‘nutrition program*’ OR ‘nutritional program*’ OR ‘nutrition educat*’ OR ‘nutritional intervention*’ OR ‘nutritional educat*’ OR ‘health disparit*’ OR poverty OR ‘social economic*’ OR socialeconomic OR hunger) AND (child* OR youth* OR adolescen* OR teen* OR preteen* OR ‘pre teen*’ OR ‘pre adolesc*’ OR preadolesc* OR boy OR boys OR girl OR girls OR schoolchild* OR ‘elementary school*’ OR ‘primary school*’ OR ‘secondary school*’ OR ‘middle school*’ OR ‘junior high*’ OR ‘high school*’ OR juvenile* OR pubescent OR ‘pre pubescent’ OR prepubescent OR kid OR kids))