# Appendix 1 Abbreviations

Table A 1 List of abbreviations

Abbreviation | Full name
BMI | Body mass index (kg/m^2^)
CNPP | Center for Nutrition Policy and Promotion
FNS | Food and Nutrition Service
HHS | United States Department of Health and Human Services
NESR | Nutrition Evidence Systematic Review
NGAD | Nutrition Guidance and Analysis Division
NGO | Non-governmental Organization
OPS | Office of Policy Support
PCS | Prospective cohort study
RCT | Randomized controlled trial
SEBTC | Summer Electronic Benefits Transfer for Children
SES | Socioeconomic status
SFSP | Summer Food Service Program
SNAP | Supplemental Nutrition Assistance Program
SNRAD | Special Nutrition Research and Analysis Division
SSB | Sugar-sweetened beverage
SSO | Seamless Summer Option
USDA | United States Department of Agriculture
WIC | Nutrition Program for Women, Infants, and Children