# List of abbreviations

Abbreviation: Full name
ADD: Attention deficit disorder
ADHD: Attention-deficit/hyperactivity disorder
ALSPAC: Avon Longitudinal Study of Parents and Children
ASD: Autism spectrum disorder
ASQ: Ages and Stages Questionnaire
BASC: Behavioral Assessment System for Children
BRIEF: Behavior Rating Inventory of Executive Functioning
BSID: Bayley Scales of Infant Development
CAST: Childhood Asperger Syndrome Test
CCCCS: Child Communication Checklist Coherence Scale
CP: Conduct problem
CPT: Continuous Performance Test
CRS-T: Conners’ Rating Scale-Teachers
DAWBA: Development and Well-Being Assessment
DDST: Denver Developmental Screening Test
DGA: Dietary Guidelines for Americans
DHA: Docosahexaenoic acid
DNBC: Danish National Birth Cohort
DSA: Delayed Spatial Alternation
EAS: Emotionality, Activity, Sociability temperament traits/scale
EOP: Early-onset conduct problem
EPA: Eicosapentaenoic acid
FFQ: Food frequency questionnaire
FTII: Fagan Infant Test
GDS: Gesell Developmental Schedules
HHS: Department of Health and Human Services
INMA: Spanish Childhood and Environment Project
IQ: Intelligence quotient
KBIT: Kaufman Brief Intelligence Test
KIDS: Kinder Infant Development Scale
MCDI: MacArthur Communicative Development Inventory
MDI: Mental Development Index
MoBa: Mother and Child Cohort Study
MSCA: McCarthy Scales of Children’s Abilities
n-3: Omega-3
NESR: Nutrition Evidence Systematic Review
NNNS: NICU Network Neurobehavioral Scale
PCS: Prospective cohort study
PDI: Psychomotor Development Index
PPVT: Peabody Picture Vocabulary Test
PUFA: Polyunsaturated fatty acid
pVEP: Pattern-reversal visual evoked potentials
SCDC: Social and Communication Disorders Checklist
SD: Standard deviation
SDQ: Strengths and Difficulties Questionnaire
SLAS: Speech and Language Assessment Scale
SON-R: Snijders-Oomen Niet-verbale Intelligentietest Revisie (Snijders-Oomen Nonverbal Intelligence Test Revision)
SRS: Social Responsiveness Scale
U.K.: United Kingdom
U.S.: United States
USDA: United States Department of Agriculture
VEXP: Visual Expectation Paradigm
WASI: Wechsler Abbreviated Scale of Intelligence
WISC: Wechsler Intelligence Scale for Children
WPPSI: Wechsler Preschool and Primary Scales of Intelligence
WRAML: Wide Range Assessment of Memory and Learning
WRAVMA: Wide Range Assessment of Visual Motor Abilities