# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^xii^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part D: Chapter 9. Dietary Fats and Seafood.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table (Table 5) provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 5 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Seafood consumption measured prior to outcome assessment; ○ Type (e.g., salmon, tuna bass); ○ Source (e.g., sea fresh water, farmed, wild); ○ Amount/frequency of intake; ○ Timing of exposure (e.g., age at intake); - Dietary intake (e.g., from food frequency questionnaires, dietary recall, fish/seafood screeners) may be validated with biomarkers for PUFA or MeHg, but not substituted. | - No measure of seafood consumption (i.e., studies that only examined biomarkers for consumption); - n-3 supplement studies which do not evaluate seafood consumption; - Studies evaluating infant formula with added DHA and/or EPA
Comparator | - Different types, sources, amounts, frequency, and/or timing of exposure of seafood consumption | - No comparator
Outcomes | - Developmental milestones, including neurocognitive development; ○ Developmental domains examined via milestone achievement and/or scales/indices, including:; ◾ cognitive,; ◾ language/communication,; ◾ movement/physical,; ◾ social/emotional; - Academic performance; - Attention deficit disorder (ADD) or attention-deficit/hyperactivity disorder (ADHD); - Anxiety; - Depression; - Autism spectrum disorder (ASD) | - No measure of neurocognitive development
Date of publication | - January 2000 to October 2019 | - Articles published prior to January 2000 or after October 2019
Publication status | - Articles that have been peer-reviewed | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals, including conference proceedings unpublished data manuscripts, reports, and abstracts
Language of publication | - Articles published in English | - Articles published in languages other than English
Country^xiii^ | - Studies conducted in countries ranked as high or very high human development | - Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants; - At intervention/exposure; ○ Females who are pregnant and/or lactating; - At outcome; ○ Males and females | - Non-human subjects (e.g., animal models or in-vitro models)
Age of study participants | - Age at outcome:; ○ Infants/toddlers (0–24 months); ○ Children/adolescents (2–18 years) | - Age at outcome:; ○ Adults (ages 19–64 years); ○ Older adults (ages 65 years and older)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease or with the neurocognitive development and/or health outcomes of interest; - Studies that enroll infants born full-term (>37 weeks and 0/7 days gestational age); - Studies that enroll some infants born preterm (gestational age <37 weeks and 0/7 days), infants with low birth weight (<2500g), and/or infants born small for gestational age | - Studies that exclusively enroll participants diagnosed with a disease or hospitalized with an illness or injury. (For this criterion, studies that exclusively enroll participants with obesity will not be excluded.); - Studies that exclusively enroll participants with the neurocognitive development and/or health outcomes of interest; - Studies that exclusively enroll infants born preterm (gestational age <37 weeks and 0/7 days), infants with low birth weight (<2500g), and/or infants born small for gestational age

### Electronic databases and search terms

Listed below are the databases and search terms searched to identify all potentially relevant articles that have been published to address this systematic review question and a second systematic review question on seafood intake during childhood and adolescence and neurocognitive development.

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: October 23, 2019
- Date range searched: January 1, 2000 - October 23, 2019
- Search Terms:
  - #1 - “Pregnancy”[Mesh] OR pregnancy OR “Pregnant Women”[Mesh] OR “pregnant women” OR pregnant OR “Lactation”[Mesh] OR lactation OR “Breast Feeding”[Mesh] OR “breast feeding” OR “Maternal Health”[Mesh] OR “maternal health” OR “Prenatal Exposure Delayed Effects”[Mesh] OR “Maternal Exposure”[Mesh] OR pregnan*[tiab] OR pre-pregnancy[tiab] OR prenatal[tiab] OR maternal OR mother* OR postpartum OR perinatal OR peri-natal OR preconception OR preconception OR peri-conception OR periconceptional OR “Peripartum Period”[Mesh] OR peripartum[tiab] OR peri-partum[tiab] OR gestation* OR natal OR puerperium[tiab] OR “Maternal Nutritional Physiological Phenomena”[Mesh] OR “Infant”[Mesh] OR infant OR “Infant, Newborn”[Mesh] OR newborn OR baby OR babies OR “Fetus”[Mesh] OR fetus OR “Child”[Mesh] OR toddler* OR child OR children OR childhood OR “Child, Preschool”[Mesh] OR preschool OR teen* OR “Adolescent”[Mesh] OR adolescent* OR “Pediatrics”[Mesh] OR pediatric*
  - #2 - Seafood OR “Seafood”[Mesh] OR seafoods OR sea-food OR “sea food” OR sea-foods OR fish OR “fish consumption” OR “Fishes”[Mesh] OR fishes OR “Fish Proteins”[Mesh] OR “fish proteins” OR “fish products” OR “fish flour” OR “fatty fish” OR shellfish OR “shellfish proteins” OR “mercury poisoning” OR “Mercury Poisoning”[Mesh] OR methylmercury OR “Sharks”[Mesh] OR sharks OR swordfish OR “Tuna”[Mesh] OR tuna OR “Salmon”[Mesh] OR salmon OR sardines OR “Gadiformes”[Mesh] OR pollock OR “Flounder”[Mesh] OR flounder OR cod OR “Tilapia”[Mesh] OR tilapia OR shrimp OR “Ostreidae”[Mesh] OR oysters OR “Mya”[Mesh] OR “Bivalvia”[Mesh] OR clams OR “Pectinidae”[Mesh] OR scallops OR “Brachyura”[Mesh] OR crab OR “Perciformes”[Mesh] OR mackerel OR “Catfishes”[Mesh] OR catfishes OR “Trout”[Mesh] OR trout OR lobster OR “Decapodiformes”[Mesh] OR squid OR halibut OR “mahi mahi” OR crawfish OR anchov* OR herring OR rockfish OR marine product* OR “Fatty Acids, Omega-3”[Mesh]
  - #3 - “Mental Disorders”[Mesh] OR mental disorder*[tiab] OR “Cognition”[Mesh] OR cognition[tiab] OR cognitive[tiab] OR metacognition[tiab] OR neurocognitive[tiab] OR neurodevelop*[tiab] OR neurological[tiab] OR “Depression”[Mesh] OR depression[tiab] OR Alzheimer*[tiab] OR senility[tiab] OR senile[tiab] OR presenile[tiab] OR “Dementia”[Mesh] OR dementia[tiab] OR anxiety[tiab] OR “Psychomotor Performance”[Mesh] OR motor skill*[tiab] OR “Executive Function”[Mesh] OR executive function* OR attention deficit disorder*[tiab] OR ADHD[tiab] OR “Child Behavior Disorders”[Mesh] OR developmental disorder*[tiab] OR “Autism Spectrum Disorder”[Mesh] OR Autism[tiab] OR Asperger[tiab] OR language processing[tiab] OR language delay* OR “Child Development”[Mesh] OR child develop*[tiab] OR developmental delay[tiab] OR developmental disabilit*[tiab] OR motor skill*[tiab] OR “Problem Solving”[Mesh] OR developmental domain* OR academic performance[tiab] Or academic achievement[tiab] OR academic failure[tiab] OR academic success*[tiab] OR “Mental Health”[Mesh] OR mental health[tiab] OR “Mental Processes”[Mesh:NoExp]
  - #4 - (#1 AND #2 AND #3)
  - #5 - (#1 AND #2 AND #3) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2000/01/01 to 2019/10/23; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: October 23, 2019
- Date range searched: January 1, 2000 - October 23, 2019
- Search Terms:
  - #1 - [mh “Pregnancy”] OR [mh “Pregnant Women”] OR [mh “Lactation”] OR [mh “Breast Feeding”] OR [mh “Maternal Health”] OR [mh “Prenatal Exposure Delayed Effects”] OR [mh “Maternal Exposure”] OR [mh “Peripartum Period”] OR [mh “Maternal Nutritional Physiological Phenomena”] OR [mh Infant] OR [mh “Infant, Newborn”] OR [mh Fetus] OR [mh Child] OR [mh “Child, Preschool”] OR [mh “Adolescent”] OR [mh “Pediatrics”]
  - #2 - (pregnan* OR lactation OR “breast feeding” OR “maternal health” OR pre-pregnancy OR prenatal OR maternal OR mother* OR postpartum OR perinatal OR peri-natal OR preconception OR preconception OR peri-conception OR periconceptional OR peripartum OR peri-partum OR gestation* OR natal OR puerperium OR infant OR newborn OR baby OR babies OR fetus OR toddler* OR child OR children OR childhood OR preschool OR teen* OR adolescent* OR pediatric*):ti,ab,kw
  - #3 - #1 OR #2
  - #4 - [mh “Seafood”] OR [mh “Fishes”] OR [mh “Fish Proteins”] OR [mh “Mercury Poisoning”] OR [mh “Sharks”] OR [mh “Tuna”] OR [mh “Salmon”] OR [mh “Gadiformes”] OR [mh “Flounder”] OR [mh “Tilapia”] OR [mh “Ostreidae”] OR [mh “Mya”] OR [mh “Bivalvia”] OR [mh “Pectinidae”] OR [mh “Brachyura”] OR [mh “Perciformes”] OR [mh “Catfishes”] OR [mh “Trout”] OR [mh “Decapodiformes”] OR [mh “Fatty Acids, Omega-3”]
  - #5 - (seafood OR seafoods OR sea-food OR “sea food” OR sea-foods OR fish OR “fish consumption” OR fishes OR “fish proteins” OR “fish products” OR “fish flour” OR “fatty fish” OR shellfish OR “shellfish proteins” OR methylmercury OR “mercury poisoning” OR sharks OR swordfish OR tuna OR salmon OR sardines OR pollock OR flounder OR cod OR tilapia OR shrimp OR oysters OR clams OR scallops OR crab OR mackerel OR catfishes OR trout OR lobster OR squid OR halibut OR “mahi mahi” OR crawfish OR anchov* OR herring OR rockfish OR marine product*):ti,ab,kw
  - #6 - #4 OR #5
  - #7 - [mh “Mental Disorders”] OR [mh “Cognition”] OR [mh “Depression”] OR [mh “Dementia”] OR [mh “Psychomotor Performance”] OR [mh “Executive Function”] OR [mh “Child Behavior Disorders”] OR [mh “Autism Spectrum Disorder”] OR [mh “Child Development”] OR [mh “Problem Solving”] OR [mh “Mental Health”] OR [mh ^“Mental Processes”]
  - #8 - (“mental disorder*” OR cognition OR cognitive OR metacognition OR neurocognitive OR neurodevelop* OR neurological OR depression OR Alzheimer* OR senility OR senile OR presenile OR dementia OR anxiety OR motor skill* OR “attention deficit disorder*” OR ADHD OR “developmental disorder*” OR Autism OR Asperger OR “language processing” OR “language delay*” OR “child develop*” OR “developmental delay” OR “developmental disabilit*” OR “motor skill*” OR “developmental domain*” OR “academic performance” OR “academic achievement” OR “academic failure” OR “academic success*” OR “mental health”):ti,ab,kw
  - #9 - #7 OR #8
  - #10 - #3 AND #6 AND #9” with Publication Year from 2000 to 2019, in Trials (Word variations have been searched)

#### Embase

- Provider: Elsevier
- Date(s) Searched: October 23, 2019
- Date range searched: January 1, 2000 - October 23, 2019
- Search Terms:
  - #1 - ‘pregnancy’/exp OR ‘pregnant woman’/exp OR ‘lactation’/exp OR ‘breast feeding’/exp OR ‘maternal welfare’/exp OR ‘prenatal exposure’/exp OR ‘mother’/exp OR ‘perinatal period’/exp OR ‘maternal nutrition’/exp OR ‘infant’/exp OR ‘newborn’/exp OR ‘baby’/exp OR ‘fetus’/exp OR ‘child’/exp OR ‘childhood’/exp OR ‘preschool’/exp OR ‘adolescent’/exp OR ‘pediatrics’/exp
  - #2 - pregnan*:ab,ti OR lactation:ab,ti OR ‘breast feeding’:ab,ti OR ‘prenatal exposure’:ab,ti OR ‘pre pregnancy’:ab,ti OR prenatal:ab,ti OR maternal:ab,ti OR mother*:ab,ti OR postpartum:ab,ti OR perinatal:ab,ti OR ‘peri natal’:ab,ti OR ‘pre conception’:ab,ti OR preconception:ab,ti OR ‘peri conception’:ab,ti OR periconceptional:ab,ti OR peripartum:ab,ti OR gestation*:ab,ti OR natal:ab,ti OR puerperium:ab,ti OR infant:ab,ti OR newborn*:ab,ti OR childhood:ab,ti OR baby:ab,ti OR babies:ab,ti OR fetus:ab,ti OR child:ab,ti OR preschool:ab,ti OR adolescent:ab,ti OR teen*:ab,ti OR pediatric*:ab,ti
  - #3 - #1 OR #2
  - #4 - ‘sea food’/exp OR ‘fish’/exp OR ‘fish consumption’/exp OR ‘fish protein’/exp OR ‘fish product’/exp OR ‘fish meal’/exp OR ‘fatty fish’/exp OR ‘shellfish’/exp OR ‘shellfish protein’/exp OR ‘mercurialism’/exp OR ‘methylmercury’/exp OR ‘shark’/exp OR ‘swordfish’/exp OR ‘tuna’/exp OR ‘salmonine’/exp OR ‘sardine’/exp OR ‘gadiformes’/exp OR ‘flounder’/exp OR ‘atlantic cod’/exp OR ‘tilapia’/exp OR ‘shrimp’/exp OR ‘oyster’/exp OR ‘mya’/exp OR ‘bivalve’/exp OR ‘clam’/exp OR ‘scallop’/exp OR ‘brachyura’/exp OR ‘crab’/exp OR ‘perciformes’/exp OR ‘mackerel’/exp OR ‘catfish’/exp OR ‘lobster’/exp OR ‘decapodiformes’/exp OR ‘squid’/exp OR ‘halibut’/exp OR ‘crayfish’/exp OR ‘anchovy’/exp OR ‘herring’/exp OR ‘rockfish’/exp OR ‘omega 3 fatty acid’/exp
  - #5 - seafood*:ab,ti OR fish:ab,ti OR ‘fish consumption’:ab,ti OR ‘fish protein*’:ab,ti OR ‘fish product*’:ab,ti OR ‘fish meal*’:ab,ti OR ‘fatty fish’:ab,ti OR ‘shellfish protein*’:ab,ti OR mercurialism:ab,ti OR methylmercury:ab,ti OR shark:ab,ti OR swordfish:ab,ti OR tuna:ab,ti OR salmonine:ab,ti OR salmon:ab,ti OR sardine*:ab,ti OR gadiformes:ab,ti OR pollock:ab,ti OR flounder:ab,ti OR cod:ab,ti OR tilapia:ab,ti OR shrimp:ab,ti OR oyster*:ab,ti OR bivalve:ab,ti OR mya:ab,ti OR clam:ab,ti OR clams:ab,ti OR scallop*:ab,ti OR crab:ab,ti OR perciformes:ab,ti OR mackerel:ab,ti OR catfish:ab,ti OR trout:ab,ti OR lobster:ab,ti OR squid:ab,ti OR decapodiformes:ab,ti OR halibut:ab,ti OR ‘mahi mahi’:ab,ti OR crayfish:ab,ti OR crawfish:ab,ti OR achov*:ab,ti OR herring:ab,ti OR rockfish:ab,ti OR ‘marine product*’:ab,ti OR ‘omega 3 fatty acid*’:ab,ti
  - #6 - #4 OR #5
  - #7 - ‘mental disease’/exp OR ‘cognition’/exp OR ‘depression’/exp OR ‘dementia’/exp OR ‘anxiety’/exp OR ‘psychomotor performance’/exp OR ‘executive function’/exp OR ‘child development’/exp OR ‘developmental disorder’/exp OR ‘psychomotor disorder’/exp OR ‘problem solving’/exp OR ‘mental health’/exp OR ‘mental function’/de
  - #8 - ‘mental disorder*’:ab,ti OR cognition:ab,ti OR cognitive:ab,ti OR metacognition:ab,ti OR neurocognitive:ab,ti OR neurodevelop*:ab,ti OR neurological:ab,ti OR depression:ab,ti OR alzheimer*:ab,ti OR senility:ab,ti OR senile:ab,ti OR presenile:ab,ti OR dementia:ab,ti OR anxiety:ab,ti OR ‘motor skill*’:ab,ti OR ‘executive function’:ab,ti OR ‘attention deficit disorder’:ab,ti OR adhd:ab,ti OR ‘developmental disorder’:ab,ti OR ‘language processing’:ab,ti OR ‘language delay*’:ab,ti OR ‘child develop*’:ab,ti OR autism:ab,ti OR asperger:ab,ti OR ‘developmental delay’:ab,ti OR ‘developmental disabilit*or developmental domain*’:ab,ti OR ‘academic performance’:ab,ti OR ‘academic achievement’:ab,ti OR ‘academic failure’:ab,ti OR ‘academic success*’:ab,ti OR ‘mental health’:ab,ti
  - #9 - #7 OR #8
  - #10 - #3 AND #6 AND #9
  - #11 - #3 AND #6 AND #9 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000–2019]/py NOT ([conference abstract]/lim OR [conference review]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

#### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) Searched: October 23, 2019
- Date range searched: January 1, 2000 - October 23, 2019
- Search Terms:
  - #S1 - (MH “Pregnancy”) OR pregnancy OR (MH “Expectant Mothers”) OR “expected mothers” OR pregnant OR (MH “Lactation”) OR lactation OR (MH “Breast Feeding”) OR breastfeeding OR (MH “Maternal-Child Health”) OR “maternal child health” OR (MH “Prenatal Exposure Delayed Effects”) OR (MH “Maternal Exposure”) OR pregnan* OR pre-pregnancy OR prenatal OR maternal OR mother OR postpartum OR perinatal OR perinatal OR pre-conception OR preconception OR peri-conception OR periconceptional OR “peripartum period” OR peripartum OR peri-partum OR gestation* OR natal OR (MH “Puerperium”) OR Puerperium OR (MH “Maternal Nutritional Physiology”) OR (MH “Infant”) OR infant OR (MH “Infant, Newborn”) OR newborn OR baby OR babies OR (MH “Fetus”) OR fetus OR (MH “Child”) OR child OR (MH “Child, Preschool”) OR toddler OR (MH “Adolescence”) OR teen* OR adolescent OR (MH “Pediatrics”) OR pediatrics
  - #S2 - seafood OR (MH “Seafood”) OR seafood* OR sea-food OR “sea food” OR (MH “Fish”) OR fish OR “fish consumption” OR fishes OR “fish protein*” OR “fish product*” OR “fish flour” OR “fatty fish” OR (MH “Shellfish”) OR shellfish OR “shellfish proteins” OR “mercury poisoning” OR (MH “Mercury Poisoning”) OR methylmercury OR shark* OR swordfish OR tuna OR salmon OR sardine* OR Pollock OR flounder OR cod OR tilapia OR shrimp OR oyster* OR clams OR scallops OR crab OR mackerel OR catfish* OR trout OR lobster* OR squid OR halibut OR “mahi mahi” OR crawfish OR achov* OR herring OR rockfish OR marine product* OR (MH “Fatty Acids, Omega-3”)
  - #S3 - (MH “Mental Disorders”) OR mental disorder* OR (MH “Cognition”) OR cognition OR cognitive OR metacognition OR neurocognitive OR neurodevelop* OR neurological OR “cognitive dysfunction” OR “depressive disorders OR (MH “Depression”) OR depression OR (MH “Alzheimer’s Disease”) OR “Alzheimer’s disease” OR (MH “Dementia, Senile”) OR senile OR senility OR presenile OR (MH “Dementia”) OR (MH “Anxiety”) OR anxiety OR (MH “Psychomotor Performance”) OR motor skill* OR (MH “Executive Function”) OR executive function* OR (MH “Attention Deficit Hyperactivity Disorder”) OR attention deficit disorder* OR ADHD OR (MH “Child Behavior Disorders”) OR developmental disorder* OR (MH “Autistic Disorder”) OR autism OR Asperger OR “language processing” OR language delay* OR (MH “Child Development”) OR child develop* OR (MH “Developmental Disabilities”) OR developmental delay* OR developmental disabilit* OR (MH “Motor Skills Disorders”) OR motor skill* OR (MH “Problem Solving”) OR developmental domain* OR “academic performance” OR “academic achievement” OR “academic failure” OR academic success* OR (MH “Mental Health”) OR “mental health” OR (MH “Mental Processes”)
  - #S4 - S1 AND S2 AND S3
  - #S5 - S1 AND S2 AND S3 NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication”) Limiters - Publication Year: 2000–2019; Peer Reviewed; English Language; Human

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining this systematic review question and a second question on seafood consumption during childhood and adolescence and neurocognitive development. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 6 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results^xiv^

### Excluded articles

The table below lists the articles excluded after full-text screening for this systematic review question and a second question on seafood consumption during childhood and adolescence and neurocognitive development, and includes columns for the categories of inclusion and exclusion criteria (see Table 5) that studies were excluded based on. At least one reason for exclusion is provided for each article, as indicated by an “X” in one of the columns, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 6 Articles excluded after full-text screening with rationale for exclusion

| Citation | Intervention/Exposure | Age | Outcome | Study Design | Comparator | Publication Status
1. | Al-Ghannami SS, Al-Adawi S, Ghebremeskel K, et al. Randomized open-label trial of docosahexaenoic acid-enriched fish oil and fish meal on cognitive and behavioral functioning in Omani children. Nutrition. 2019;57:167–172. doi:10.1016/j.nut.2018.04.008. | | | | | X
2. | Andrew MJ, Parr JR, Montague-Johnson C, et al. Nutritional intervention and neurodevelopmental outcome in infants with suspected cerebral palsy: the Dolphin infant double-blind randomized controlled trial. Dev Med Child Neurol. 2018;60(9):906–913. doi:10.1111/dmcn.13586. | X
3. | Boucher O, Muckle G, Ayotte P, Dewailly E, Jacobson SW, Jacobson JL. Altered fine motor function at school age in Inuit children exposed to PCBs, methylmercury, and lead. Environ Int. 2016;95:144–51. doi:10.1016/j.envint.2016.08.010. | X
4. | Braarud HC, Markhus MW, Skotheim S, et al. Maternal DHA Status during Pregnancy Has a Positive Impact on Infant Problem Solving: A Norwegian Prospective Observation Study. Nutrients. 2018;10(5). pii: E529. doi:10.3390/nu10050529. | X
5. | Brouwer-Brolsma EM, van de Rest O, Godschalk R, Zeegers MPA, Gielen M, de Groot RHM. Associations between maternal long-chain polyunsaturated fatty acid concentrations and child cognition at 7 years of age: The MEFAB birth cohort. Prostaglandins Leukot Essent Fatty Acids. 2017;126:92–97. doi:10.1016/j.plefa.2017.09.012. | X
6. | Budtz-Jorgensen E, Grandjean P, Weihe P. Separation of risks and benefits of seafood intake. Environ Health Perspect. 2007;115(3):323–7. doi:10.1289/ehp.9738. | | | | X
7. | Butler LJ, Janulewicz PA, Carwile JL, White RF, Winter MR, Aschengrau A. Childhood and adolescent fish consumption and adult neuropsychological performance: An analysis from the Cape Cod Health Study. Neurotoxicol Teratol. 2017;61:47‐57. doi:10.1016/j.ntt.2017.03.001. | | | | X
8. | Carwile JL, Butler LJ, Janulewicz PA, Winter MR, Aschengrau A. Childhood Fish Consumption and Learning and Behavioral Disorders. Int J Environ Res Public Health. 2016;13(11):1069. doi:10.3390/ijerph13111069 | | | | X
9. | Chen MYY, Wong, WWK, et al. Quantitative risk-benefit analysis of fish consumption for women of child-bearing age in Hong Kong. Food Addit Contam Part A Chem Anal Control Exp Risk Assess. 2014;31(1):48–53. doi:10.1080/19440049.2013.855947. | | | X
10. | Chien LC, Gao CS, Lin HH. Hair mercury concentration and fish consumption, Risk and perceptions of risk among women of childbearing age. Environ Res. 2010;110(1):123–129. doi:10.1016/j.envres.2009.10.001. | | | X | X
11. | Choi AL, Mogensen UB, Bjerve KS, et al. Negative confounding by essential fatty acids in methylmercury neurotoxicity associations. Neurotoxicol Teratol. 2014;42,85–92. doi:10.1016/j.ntt.2014.02.003. | X
12. | Davidson PW, Cory-Slechta DA, Thurston SW, et al. Fish consumption and prenatal methylmercury exposure, cognitive and behavioral outcomes in the main cohort at 17 years from the Seychelles child development study. Neurotoxicology. 2011;32(6):711–7. doi:10.1016/j.neuro.2011.08.003. | X | X
13. | Davidson PW, Kost J, Myers GJ, Cox C, Clarkson TW, Shamlaye, C. F. Methylmercury and neurodevelopment, reanalysis of the Seychelles Child Development Study outcomes at 66 months of age. JAMA. 2001;285(10):1291–3. doi:10.1001/jama.285.10.1291. | | | | X
14. | Davidson PW, Leste A, Benstrong E, et al. Fish consumption, mercury exposure, and their associations with scholastic achievement in the Seychelles Child Development Study. Neurotoxicology. 2010;31(5):439–47. doi:10.1016/j.neuro.2010.05.010. | X
15. | de Groot RH, Ouwehand C, Jolles J. Eating the right amount of fish, inverted U-shape association between fish consumption and cognitive performance and academic achievement in Dutch adolescents. Prostaglandins Leukot Essent Fatty Acids. 2012;86(3):113–7. doi:10.1016/j.plefa.2012.01.002. | | | | X
16. | Debes F, Budtz-Jorgensen E, Weihe P, White RF, Grandjean P. Impact of prenatal methylmercury exposure on neurobehavioral function at age 14 years. Neurotoxicol Teratol. 2006;28(5):536–47. doi:10.1016/j.ntt.2006.02.005. | X
17. | Debes F, Weihe P, Grandjean P. Cognitive deficits at age 22 years associated with prenatal exposure to methylmercury. Cortex. 2016;74,358–69. doi:10.1016/j.cortex.2015.05.017. | X | X
18. | Dorea JG, Marques RC, Abreu L. Milestone achievement and neurodevelopment of rural Amazonian toddlers (12 to 24 months) with different methylmercury and ethylmercury exposure. J Toxicol Environ Health A. 2014;77:1–13. doi:10.1080/15287394.2014.861335. | X | | | X
19. | Dye D. Mother’s omega-3 fatty acid deficit impairs infant’s X neurological development. Life Extension. 2008;14:28–28. | | | | | | X
20. | Emmett PM. Dietary Patterns during Complementary Feeding and Later Outcomes. Nestle Nutr Inst Workshop Ser. 2016;85:145–54. doi:10.1159/000439505. | X | | | X
21. | Emmett PM, Jones LR, Golding J. Pregnancy diet and associated outcomes in the Avon Longitudinal Study of Parents and Children. Nutr Rev. 2015;73(Suppl 3):154–74. doi:10.1093/nutrit/nuv053. | | | | X
22. | Freire C, Ramos R, Lopez-Espinosa MJ, et al.. Hair mercury levels, fish consumption, and cognitive development in preschool children from Granada Spain. Environ Res. 2010;110(1):96–104. doi:10.1016/j.envres.2009.10.005. | X | | | X
23. | Gao L, Cui SS, Han Y, Dai W, Su YY, Zhang X. Does periconceptional fish consumption by parents affect the incidence of Autism Spectrum Disorder and intelligence deficiency? A case-control study in Tianjin, China. Biomed Environ Sci. 2016;29(12):885–892. doi:10.3967/bes2016.118. | | | | X
24. | Gao L, Xi QQ, Wu J, et al. Association between prenatal environmental factors and child Autism: A case control study in Tianjin, China. Biomed Environ Sci. 2015;28(9):642–50. doi:10.3967/bes2015.090. | | | | X
25. | Gao Y, Yan CH, Tian Y, et al. Prenatal exposure to mercury and neurobehavioral development of neonates in Zhoushan City, China. Environ Res. 2007;105(3):390–9. doi:10.1016/j.envres.2007.05.015. | X | | | | X
26. | Gari M, Grimalt JO, Torrent M, Sunyer J. Influence of socio-demographic and diet determinants on the levels of mercury in preschool children from a Mediterranean island. Environ Pollut. 2013;182:291–8. doi:10.1016/j.envpol.2013.07.022. | X | | | X
27. | Gignac F, Romaguera D, Fernandez-Barres S, Phillipat C, et al. Maternal nut intake in pregnancy and child neuropsychological development up to 8 years old: a population-based cohort study in Spain. Eur J Epidemiol. 2019;34(7):661–673. doi:10.1007/s10654-019-00521-6. | X
28. | Gispert-Llaurado M, Perez-Garcia M, Escribano J, et al. Fish consumption in mid-childhood and its relationship to neuropsychological outcomes measured in 7–9 year old children using a NUTRIMENTHE neuropsychological battery. Clin Nutr. 2016;35(6):1301–1307. doi:10.1016/j.clnu.2016.02.008. | | | | X
29. | Golding J, Gregory S, Ellis G, et al. Maternal prenatal external locus of control and reduced mathematical and science abilities in their offspring: A longitudinal birth cohort study. Front Psychol. 2019;10:194. doi:10.3389/fpsyg.2019.00194. | X | | | | X
30. | Golding J, Gregory S, Iles-Caven Y, Hibbeln J, Emond A, Taylor CM. Associations between prenatal mercury exposure and early child development in the ALSPAC study. Neurotoxicology. 2016;53:215–222. doi:10.1016/j.neuro.2016.02.006. | | | | | X
31. | Golding J, Hibbeln JR, Gregory SM, Iles-Caven Y, Emond A, Taylor CM. Maternal prenatal blood mercury is not adversely associated with offspring IQ at 8 years provided the mother eats fish: A British prebirth cohort study. Int J Hyg Environ Health. 2017;220(7):1161–1167. doi:10.1016/j.ijheh.2017.07.004. | X | | | | X
32. | Groth E 3rd. Re: ‘Maternal fish intake during pregnancy, blood mercury levels, and child cognition at age 3 years in a US cohort’. Am J Epidemiol. 2008;168(2):236. doi:10.1093/aje/kwn172. | | | | X
33. | Haapala EA, Eloranta AM, Venalainen T, et al. Diet quality and academic achievement: a prospective study among primary school children. Eur J Nutr. 2017;56(7):2299–2308. doi:10.1007/s00394-016-1270-5. | X
34. | Halldorsson TI, Thorsdottir I, Meltzer HM, Strom M, Olsen SF. Dioxin-like activity in plasma among Danish pregnant women: dietary predictors, birth weight and infant development. Environ Res. 2009;109(1):22–8. doi:10.1016/j.envres.2008.08.011. | X | | | | X
35. | Hamazaki T, Hirayama S. The effect of docosahexaenoic acid-containing food administration on symptoms of attention-deficit/hyperactivity disorder-a placebo-controlled double-blind study. Eur J Clin Nutr. 2004; 58(5):838. doi:10.1038/sj.ejcn.1601888. | | | | X
36. | Handeland K, Skotheim S, Baste V, et al. The effects of fatty fish intake on adolescents’ nutritional status and associations with attention performance: Results from the FINS-TEENS randomized controlled trial. Nutr J. 2018;17(1):30. doi:10.1186/s12937-018-0328-z. | | | | X
37. | Hart SL, Boylan LM, Carroll SR, et al. Brief report: newborn X behavior differs with decosahexaenoic acid levels in breast milk. J Pediatr Psychol. 2006;31(2):221–6. doi:10.1093/jpepsy/jsj069. | X | | | X
38. | Henriksen C, Haugholt K, Lindgren, M, et al. Improved cognitive development among preterm infants attributable to early supplementation of human milk with docosahexaenoic acid and arachidonic acid. Pediatrics. 2008;121(6):1137–45. doi:10.1542/peds.2007-1511. | X
39. | Hertz-Picciotto I, Green PG, Delwiche L, Hansen R, Walker C, Pessah IN. Blood mercury concentrations in CHARGE Study children with and without autism. Environ Health Perspect. 2010;118(1):161–6. doi:10.1289/ehp.0900736. | X | | | X
40. | Hibbeln JR, Davis JM. Considerations regarding neuropsychiatric nutritional requirements for intakes of omega-3 highly unsaturated fatty acids. Prostaglandins Leukot Essent Fatty Acids. 2009;81(2–3):179–86. doi:10.1016/j.plefa.2009.06.005. | X | | | X
41. | Hibbeln J, Gregory S, Iles-Caven Y, Taylor CM, Emond A, Golding J. Total mercury exposure in early pregnancy has no adverse association with scholastic ability of the offspring particularly if the mother eats fish. Environ Int. 2018;116:108–115. doi:10.1016/j.envint.2018.03.024. | X | | | | X
42. | Hoerr J, Fogel J, Van Voorhees B. Ecological correlations of dietary food intake and mental health disorders. J Epidemiol Glob Health. 2017;7(1):81–89. doi:10.1016/j.jegh.2016.12.001. | | | | X | X
43. | Hsi HC, Jiang CB, Yang TH, Chien LC. The neurological effects of prenatal and postnatal mercury/methylmercury exposure on three-year-old children in Taiwan. Chemosphere. 2014;100:71–6. doi:10.1016/j.chemosphere.2013.12.068. | X | | | X
44. | Iles-Caven Y, Golding J, Gregory S, Emond A, Taylor CM. Data relating to early child development in the Avon Longitudinal Study of Parents and Children (ALSPAC), their relationship with prenatal blood mercury and stratification by fish consumption. Data Brief. 2016;9:112–22. doi:10.1016/j.dib.2016.08.034. | | | | X | X
45. | Innis SM, Friesen RW. Essential n-3 fatty acids in pregnant women and early visual acuity maturation in term infants. Am J Clin Nutr. 2008;87(3):548–557. doi:10.1093/ajcn/87.3.548. | X
46. | Jacobson JL, Jacobson SW. Prenatal exposure to polychlorinated biphenyls and attention at school age. J Pediatr. 2003;143(6):780–8. doi:10.1067/S0022-3476(03)00577-8. | X
47. | Jedrychowski W, Perera F, Jankowski J, et al. Fish consumption in pregnancy, cord blood mercury level and cognitive and psychomotor development of infants followed over the first three years of life, Krakow epidemiologic study. Environ Int. 2007;33(8):1057–62. doi:10.1016/j.envint.2007.06.001. | X | | | | X
48. | Jensen TK, Grandjean P, Jorgensen EB, White RF, Debes F, Weihe P. Effects of breast feeding on neuropsychological development in a community with methylmercury exposure from seafood. J Expo Anal Environ Epidemiol. 2005;15(5):423–30. doi:10.1038/sj.jea.7500420. | X
49. | Kim Y, Ha EH, Park H, et al. Prenatal mercury exposure, fish intake and neurocognitive development during first three years of life, Prospective cohort mothers and Children’s environmental health (MOCEH) study. Sci Total Environ. 2018;615:1192–1198. doi:10.1016/j.scitotenv.2017.10.014. | X | | | | X
50. | Kishi R, Araki A, Minatoya M, et al. The Hokkaido Birth Cohort Study on Environment and Children’s Health, cohort profile-updated 2017. Environ Health Prev Med. 2017;22(1):46. doi:10.1186/s12199-017-0654-3. | X
51. | Lam HS, Fok TF, Ng PC. Long-term neurocognitive outcomes of children prenatally exposed to low-dose methylmercury. Hong Kong Med J. 2012;18(Suppl 6):S23–4. | X | X
52. | Lauritzen L, Jorgensen MH, Olsen SF, Straarup EM, Michaelsen KF. Maternal fish oil supplementation in lactation, effect on developmental outcome in breast-fed infants. Reprod Nutr Dev. 2005;45(5):535–47. doi:10.1051/rnd:2005044. | X | | | | X
53. | Llop S, Ballester F, Murcia M, et al. Prenatal exposure to mercury and neuropsychological development in young children, the role of fish consumption. Int J Epidemiol. 2017;46(3):827–838. doi:10.1093/ije/dyw259. | X | | | | X
54. | Loring PA, Duffy LK, Murray MS. A risk-benefit analysis of wild fish consumption for various species in Alaska reveals shortcomings in data and monitoring needs. Sci Total Environ. 2010;408(20):4532–41. doi:10.1016/j.scitotenv.2010.07.013. | | | | X
55. | Lyall K, Munger KL, O’Reilly EJ, Santangelo SL, Ascherio A. Maternal dietary fat intake in association with autism spectrum disorders. Am J Epidemiol. 2013;178(2):209–20. doi:10.1093/aje/kws433. | X | X
56. | Lynch ML, Huang LS, Cox C, et al. Varying coefficient function models to explore interactions between maternal nutritional status and prenatal methylmercury toxicity in the Seychelles Child Development Nutrition Study. Environ Res 2011;111(1):75–80. doi:10.1016/j.envres.2010.09.005. | X | | | X
57. | Mamalakis G, Kiriakakis M, Tsibinos G, Kafatos A. Depression and adipose polyunsaturated fatty acids in an adolescent group. Prostaglandins Leukot Essent Fatty Acids. 2004;71(5):289–94. doi:10.1016/j.plefa.2004.04.002. | X
58. | Marques RC, Abreu L, Bernardi JV, Dorea JG. Traditional living in the Amazon, Extended breastfeeding, fish consumption, mercury exposure and neurodevelopment. Ann Hum Biol. 2016;43(4):360–70. doi:10.1080/03014460.2016.1189962. | X
59. | Marques RC, Dorea JG, Leao RS, et al. Role of methylmercury exposure (from fish consumption) on growth and neurodevelopment of children under 5 years of age living in a transitioning (tin-mining) area of the western Amazon, Brazil. Arch Environ Contam Toxicol. 2012;62(2):341–50. doi:10.1007/s00244-011-9697-4. | | X | | X
60. | Marques RC, Garrofe Dorea J, Rodrigues Bastos W, de Freitas Rebelo M, de Freitas Fonseca M, Malm O. Maternal mercury exposure and neuro-motor development in breastfed infants from Porto Velho (Amazon), Brazil. Int J Hyg Environ Health. 2007;210(1):51–60. doi:10.1016/j.ijheh.2006.08.001. | X
61. | Matsudaira T. Attention deficit disorders-drugs or nutrition?. Nutr Health. 2007;19(1–2):57–60. doi:10.1177/026010600701900206. | | | | X
62. | McGuire J, Kaplan J, Lapolla J, Kleiner R. The 2014 FDA assessment of commercial fish, practical considerations for improved dietary guidance. Nutr J. 2016;15(1):66. doi:10.1186/s12937-016-0182-9. | | | | X
63. | Milte CM, Sinn N, Buckley JD, Coates AM, Young RM, Howe PRC. Polyunsaturated fatty acids, cognition and literacy in children with ADHD with and without learning difficulties. J Child Health Care. 2011;15(4):299–311. doi:10.1177/1367493511403953. | X
64. | Myers GJ, Davidson PW. Maternal fish consumption benefits children’s development. Lancet. 2007;369(9561):537–8. doi:10.1016/S0140-6736(07)60248-7. | | | | X
65. | Ng KH, Meyer BJ, Reece L, Sinn N. Dietary PUFA intakes in children with attention-deficit/hyperactivity disorder symptoms. Br J Nutr. 2009;102(11):1635–41. doi:10.1017/S0007114509990821. | | | | X | X
66. | Ninger LJ. Fish oil improves infants’ cognitive and motor function. Life Extension. 2008;14,23–23. | | | | | | X
67. | Noaghiul S, Hibbeln JR. Cross-national comparisons of seafood consumption and rates of bipolar disorders. Am J Psychiatry. 2003;160(12):2222–7. doi:10.1176/appi.ajp.160.12.2222. | | | X | X
68. | Oddy WH, Allen KL, Trapp GSA, et al. Dietary patterns, body mass index and inflammation, Pathways to depression and mental health problems in adolescents. Brain Behav Immun. 2018;69:428–439. doi:10.1016/j.bbi.2018.01.002. | X
69. | Oddy WH, Hickling S, Smith MA, et al. Dietary intake of omega-3 fatty acids and risk of depressive symptoms in adolescents. Depress Anxiety. 2011;28(7):582–8. doi:10.1002/da.20822. | X
70. | Pawelczyk T, Trafalska E, Kotlicka-Antczak M, Pawelczyk A. The association between polyunsaturated fatty acid consumption and the transition to psychosis in ultra-high risk individual. Prostaglandins Leukot Essent Fatty Acids. 2016;108:30–7. doi:10.1016/j.plefa.2016.03.010. | X | | X
71. | Qi Y, Niu J. Does childhood nutrition predict health outcomes during adulthood? Evidence from a population-based study in China. J Biosoc Sci. 2015;47(5):650–66. doi:10.1017/S0021932014000509. | X | | | X
72. | Rahbar MH, Samms-Vaughan M, Loveland KA, et al. Seafood consumption and blood mercury concentrations in Jamaican children with and without autism spectrum disorders. Neurotox Res. 2013;23(1):22–38. doi:10.1007/s12640-012-9321-z. | | | | X
73. | Rees AM, Austin MP, Parker GB. Omega-3 fatty acids as a treatment for perinatal depression, randomized double-blind placebo-controlled trial. Aust N Z J Psychiatry. 2008; 42(3):199–205. doi:10.1080/00048670701827267. | X
74. | Rees A, Sirois S, Wearden A. Maternal docosahexaenoic acid intake levels during pregnancy and infant performance on a novel object search task at 22 months. Child Dev. 2014;85(6):2131–9. doi:10.1111/cdev.12280. | X | X
75. | Rioux FM, Belanger-Plourde J, Leblanc CP, Vigneau F. Relationship between maternal DHA and iron status and infants’ cognitive performance. Can J Diet Pract Res. 2011;72,76. | X
76. | Samson K. Cognitive benefits of seafood during pregnancy outweigh risk, new study finds. Neurology Today. 2007;7(5):35–36. | | | | X
77. | Schell JD, Jr, Budinsky RA, Wernke MJ. PCBs and neurodevelopmental effects in Michigan children, an evaluation of exposure and dose characterization. Regul Toxicol Pharmacol. 2001;33(3):300–12. doi:10.1006/rtph.2001.1475. | | | | X
78. | Schmiedel V, Vogt H, Walach H. Are pupils’ ‘Programme for International Student Assessment (PISA)’ scores associated with a nation’s fish consumption?. Scand J Public Health. 2018;46(7):675–679. doi:10.1177/1403494817717834. | | | | X
79. | Seafood in pregnancy: good or bad for the offspring?. Child Health Alert. 2007;25:1–3. | | | | X
80. | Skotheim S, Dahl L, Handeland K, et al. Design of the FINS-TEENS study: A randomized controlled trial assessing the impact of fatty fish on cognitive performance in adolescents. Scand J Public Health. 2017; 45(6):621–629. doi:10.1177/1403494817717408. | | | X
81. | Sorensen LB, Damsgaard CT, Dalskov SM, et al. Diet-induced changes in iron and n-3 fatty acid status and associations with cognitive performance in 8–11-year-old Danish children: secondary analyses of the Optimal Well-Being, Development and Health for Danish Children through a Healthy New Nordic Diet School Meal Study. Br J Nutr. 2015;114(10):1623–37. doi:10.1017/S0007114515003323. | X
82. | Steuerwald U, Weihe P, Jorgensen PJ, et al. Maternal seafood diet, methylmercury exposure, and neonatal neurologic function. J Pediatr. 2000;136(5):599–605. doi:10.1067/mpd.2000.102774 | X | | X
83. | Stewart PW, Lonky E, Reihman J, Pagano J, Gump BB, Darvill T. The relationship between prenatal PCB exposure and intelligence (IQ) in 9-year-old children. Environ Health Perspect. 2008;116(10):1416–22. doi:10.1289/ehp.11058. | X
84. | Strain JJ, Davidson PW, Thurston SW, et al. Maternal PUFA status but not prenatal methylmercury exposure is associated with children’s language functions at age five years in the Seychelles. J Nutr. 2012;142(11):1943–9. doi:10.3945/jn.112.163493. | X | X
85. | Surkan PJ, Wypij D, Trachtenberg F, et al. Neuropsychological X function in school-age children with low mercury exposures. Environ Res. 2009;109(6):728–33. doi:10.1016/j.envres.2009.04.006. | X | | | X
86. | Suzuki K, Nakai K, Sugawara T, et al. Neurobehavioral effects of prenatal exposure to methylmercury and PCBs, and seafood intake: neonatal behavioral assessment scale results of Tohoku study of child development. Environ Res. 2010;110(7):699–704. doi:10.1016/j.envres.2010.07.001. | X
87. | Tatsuta N, Murata K, Iwai-Shimada M, Yaginuma-Sakurai K, Satoh H, Nakai K. Psychomotor ability in children prenatally exposed to methylmercury: The 18-month follow-up of Tohoku Study of Child Development. Tohoku J Exp Med. 2017;242(1):1–8. doi:10.1620/tjem.242.1. | X
88. | Tatsuta N, Nakai K, Sakamoto M, Murata K, Satoh H. Methylmercury exposure and developmental outcomes in Tohoku Study of Child Development at 18 months of age. Toxics. 2018;6(3). pii: E49. doi:10.3390/toxics6030049. | X | | | | X
89. | Theobald H. Oily fish and pregnancy. Nutrition Bulletin. 2003;28,247–251. | X | | | X
90. | Timonen M, Horrobin D, Jokelainen J, Laitinen J, Herva A, Rasanen P. Fish consumption and depression: the Northern Finland 1966 birth cohort study. J Affect Disord. 2004;82(3):447–52. doi:10.1016/j.jad.2004.02.002 | | X
91. | Tomlinson D, Wilkinson H, Wilkinson P. Diet and mental health in children. Child Adolesc Ment Health. 2009;14(3):148–55. doi:10.1111/j.1475-3588.2008.00520.x. | | | | X
92. | Vacchi-Suzzi C, Karimi R, Kruse D, et al. Low-level mercury, omega-3 index and neurobehavioral outcomes in an adult US coastal population. Eur J Nutr. 2016;55(2):699–711. doi:10.1007/s00394-015-0890-5. | | X
93. | Valent F, Horvat M, Sofianou-Katsoulis A, et al. Neurodevelopmental effects of low-level prenatal mercury exposure from maternal fish consumption in a Mediterranean cohort: study rationale and design. J Epidemiol. 2013;23(2):146–52. doi:10.2188/jea.JE20120030. | | | X | X
94. | van Wijngaarden E, Thurston SW, Myers GJ, et al. Prenatal methyl mercury exposure in relation to neurodevelopment and behavior at 19 years of age in the Seychelles Child Development Study. Neurotoxicol Teratol. 2013;39:19–25. doi:10.1016/j.ntt.2013.06.003 | X | X
95. | Vejrup K, Schjolberg S, Knutsen HK, et al. Prenatal methyl mercury exposure and language delay at three years of age in the Norwegian Mother and Child Cohort Study. Environ Int. 2016;92:63–9. | X | | | | X
96. | Waylen A, Ford T, Goodman R, Samara M, Wolke D. Can early intake of dietary omega-3 predict childhood externalizing behaviour?. Acta Paediatr. 2009;98(11):1805–8. doi:10.1111/j.1651-2227.2009.01434.x. | X
97. | Woo HD, Kim DW, Hong YS, et al. Dietary patterns in children with attention deficit/hyperactivity disorder (ADHD). Nutrients. 2014;6(4):1539–53. doi:10.3390/nu6041539. | | | | X
98. | Wu J, Ying T, Shen Z, Wang H. Effect of low-level prenatal mercury exposure on neonate neurobehavioral development in China. Pediatr Neurol. 2014;51(1):93–9. doi:10.1016/j.pediatrneurol.2014.03.018 | | X | | | X
99. | Zeilmaker MJ, Hoekstra J, van Eijkeren JC, et al. Fish consumption during child bearing age: a quantitative risk-benefit analysis on neurodevelopment. Food Chem Toxicol. 2013;54:30–4. doi:10.1016/j.fct.2011.10.068 | | | | X
100. | Zhou F, Wu F, Zou S, Chen Y, Feng C, Fan G. Dietary, nutrient patterns and blood essential elements in Chinese children with ADHD. Nutrients. 2016;8(6). pii: E352. doi:10.3390/nu8060352. | | | | X

xii Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xiii The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990–2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending group) Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).

xiv Two articles were included in both the review for pregnancy and lactation and the review for childhood and adolescence