# List of abbreviations

Abbreviation: Full name
9-HPT: 9-Hole Peg Test
ADD: Attention deficit disorder
ADHD: Attention-deficit/hyperactivity disorder
ALSPAC: Avon Longitudinal Study of Parents and Children
ASD: Autism spectrum disorder
CLASS: Children’s Lifestyle and School Performance Study
DHA: Docosahexaenoic acid
EPA: Eicosapentaenoic acid
FFQ: Food frequency questionnaire
FINS-KIDS: Fish Intervention Studies-KIDS
FINS-TEENS: Fish Intervention Studies-TEENS
HHS: United States Department of Health and Human Services
IQ: Intelligence quotient
IQR: Interquartile range
MFQ: Moods and Feeling Questionnaire
n-3: Omega-3
NESR: Nutrition Evidence Systematic Review
PCS: Prospective cohort study
RCT: Randomized controlled trial
SD: Standard deviation
SDQ: Strengths and Difficulties Questionnaire
THHg: Total hair mercury concentration
U.K.: United Kingdom
U.S.: United States
USDA: United States Department of Agriculture
WISC: Wechsler Intelligence Scale for Children
WPPSI: Wechsler Preschool and Primary Scales of Intelligence