# List of abbreviations

Abbreviation: Full name
BMI: Body mass index
CHD: Coronary heart disease
CVD: Cardiovascular disease
HDL: High-density lipoprotein
HHS: United States Department of Health and Human Services
LDL: Low-density lipoprotein
NESR: Nutrition Evidence Systematic Review
PCS: Prospective cohort study
RCT: Randomized controlled trial
SD: Standard deviation
TC: Total cholesterol
U.K.: United Kingdom
U.S.: United States
USDA: United States Department of Agriculture