# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^vii^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part D. Chapter 9. Dietary Fats and Seafood.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on the relationship between seafood consumption during childhood and adolescence (up to 18 years of age) and risk of cardiovascular disease. For this systematic review, the target population considered was infants and toddlers (birth to 24 months), children and adolescents (ages 2-18 years), full-term, healthy and/or at risk for chronic disease for the intervention/exposure; children and adolescents (ages 2-18 years), adults (ages 19-64 years), and older adults (ages 65 years and older) for the intermediate CVD outcome, and adults (ages 19-64) and older adults (65 years and older) for the CVD endpoint outcome. The interventions or exposures considered were seafood consumption (type, source, amounts, frequency, and/or timing of exposure) and their comparators were different types, sources, and/or amounts of seafood consumed; different frequency of and/or timing of seafood consumption. The intermediate outcomes considered were blood pressure (systolic and diastolic), total cholesterol, LDL-cholesterol, HDL-cholesterol, (including TC:HDL and LDL:HDL ratios) and triglycerides. The outcomes considered were cardiovascular disease (CVD): myocardial infarction, coronary heart disease, coronary artery disease, congestive heart failure, peripheral artery disease), venous thrombosis, and cardiovascular-related mortality. The key confounders were Child sex, Child age, Race/ethnicity, Socioeconomic status, Non-fish dietary exposure to n-3 PUFAs, Smoking, Anthropometry, and Family history of CVD. The key covariates were key nutrients in seafood (e.g., n-3 PUFAs, iron, iodine, selenium, fish protein, vitamin D); Environmental chemicals, e.g., mercury, persistent organic pollutants, and polychlorinated biphenyls; Blood and human milk biomarkers of seafood intake (e.g., n-3 PUFAs, and environmental pollutants).

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table (Table 4) provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 4 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Seafood consumption measured prior to outcome assessment; ○ Type (e.g., salmon, tuna, bass); ○ Source (e.g., sea, fresh water, farmed, wild); ○ Amount/frequency of intake; ○ Timing of exposure (e.g., age at intake); ○ Dietary intake (e.g., from food frequency questionnaires, dietary recall, fish/seafood screeners) may be validated with biomarkers for polyunsaturated fatty acid or methylmercury, but not substituted. | - No measure of seafood consumption (i.e., studies that only examined biomarkers for consumption); - omega-3 supplement studies which do not evaluate seafood consumption; - Studies evaluating infant formula with added docosahexaenoic acid (DHA) and/or eicosapentaenoic acid (EPA)
Comparator | - Different types, sources, amounts, frequency, and/or timing of exposure of seafood consumption | - No comparator
Outcomes | - Intermediate Outcomes; ○ Blood pressure (systolic and diastolic); ○ Total Cholesterol (TC); ○ LDL-Cholesterol; ○ HDL-Cholesterol (including TC:HDL and LDL:HDL ratios); ○ Triglycerides; - Endpoint Outcomes; ○ Cardiovascular disease (myocardial infarction, coronary heart disease, coronary artery disease, congestive heart failure, peripheral artery disease); ○ Stroke; ○ Venous thrombosis; ○ Cardiovascular disease mortality
Date of publication | - January 2000 to July 2019 | - Articles published prior to January 2000 or after July 2019
Publication status | - Articles that have been peer-reviewed | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, reports, abstracts, and conference proceedings
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^viii^ | - Studies conducted in countries ranked as high or very high human development | - Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants | - Non-human subjects (e.g., animal models or in-vitro models)
Age of study participants | - Age at intervention or exposure:; ○ Infants and toddlers (0-24 months); ○ Children and adolescents (ages 2-18 years); - Age at intermediate outcomes:; ○ Children and adolescents (ages 2-18 years); ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older); - Age at endpoint outcomes:; ○ Adults (ages 19-64 years); ○ Older adults (ages 65 years and older)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that exclusively enroll participants with high blood pressure or high cholesterol and are evaluating cardiovascular disease endpoint outcomes; - Studies that enroll some participants diagnosed with cardiovascular disease endpoint outcomes.; - Studies that enroll some participants diagnosed with a disease or hospitalized with and illness or injury; - Studies that enroll infants born full-term (≥37 weeks and 0/7 days gestational age); - Studies that enroll some infants born preterm (gestational age <37 weeks and 0/7 days), infants with low birth weight (<2500g), and/or infants born small for gestational age | - Studies that exclusively enroll participants diagnosed with a disease (e.g., diabetes, renal disease), or hospitalized with an illness or injury (For this criterion, studies that exclusively enroll participants with obesity will not be excluded); - Studies that exclusively enroll participants with cardiovascular disease endpoint outcomes (i.e., studies that aim to treat participants who have already been diagnosed with cardiovascular disease); - Studies that exclusively enroll participants with high blood pressure or high cholesterol and are evaluating blood pressure or cholesterol outcomes (i.e., studies that aim to treat participants who already have high blood pressure or high cholesterol)

### Electronic databases and search terms

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: July 29, 2019
- Date range searched: January 1, 2000-July 29, 2019
- Search Terms:
  - #1 - “Seafood”[Mesh] OR seafood* OR sea food* OR “fish consumption” OR “Fishes”[Mesh] OR fish[tiab] OR fishes[tiab] OR “fish products” OR fatty fish[tiab] OR shellfish[tiab] OR “Fish Proteins, Dietary”[Mesh] OR shellfish protein* OR “Mercury Poisoning”[Mesh] OR mercury poisoning* OR methylmercury[tiab] OR sharks[tiab] OR swordfish[tiab] OR tuna[tiab] OR salmon[tiab] OR sardines[tiab] OR pollock[tiab] OR flounder[tiab] OR cod[tiab] OR tilapia[tiab] OR shrimp[tiab] OR “Ostreidae”[Mesh] OR oysters[tiab] OR “Mya”[Mesh] OR “Bivalvia”[Mesh] OR clams[tiab] OR “Pectinidae”[Mesh] OR scallops[tiab] OR “Brachyura”[Mesh] OR crab[tiab] OR mackerel[tiab] OR catfish*[tiab] OR trout[tiab] OR lobster[tiab] OR “Decapodiformes”[Mesh] OR squid[tiab] OR halibut[tiab] OR “mahi mahi” OR crawfish[tiab] OR anchov*[tiab] OR herring[tiab] OR rockfish OR marine product* OR “Fatty Acids, Omega-3”[Mesh]
  - #2 - “Cardiovascular Diseases”[Mesh:NoExp] OR cardiovascular disease*[tiab] OR coronary artery disease[tiab] OR heart disease*[tiab] OR “Heart Failure”[Mesh] OR heart failure[tiab] OR “Myocardial Infarction”[Mesh] OR myocardial infarction*[tiab] OR “Myocardial Ischemia”[Mesh] OR Myocardial Ischemia*[tiab] OR “Stroke”[Mesh] OR stroke[tiab] OR angina[tiab] OR heart attack[tiab] OR “Venous Thrombosis”[Mesh] OR venous thrombosis[tiab] OR hypertension[tiab] OR high blood pressure[tiab] OR “Lipids/blood”[Mesh] OR “Cholesterol, HDL”[Mesh] OR HDL cholesterol[tiab] OR “Cholesterol, LDL”[Mesh] OR LDL cholesterol[tiab] OR total cholesterol[tiab] OR “Triglycerides”[Mesh] OR triglycerides[tiab]
  - #3 - “Child”[Mesh] OR child[tiab] OR children[tiab] OR youth* OR “Adolescent”[Mesh] OR adolescence[tiab] OR adolescent* OR teen[tiab] OR teens[tiab] OR teenager* OR preteen* OR pre-teen* OR pre-adolesc* OR preadolesc* OR preschool* OR pediatric* OR paediatric* OR boy[tiab] OR boys[tiab] or girl[tiab] OR girls[tiab] OR schoolchild* OR middle school* OR high school* OR juvenile[tiab] OR pubescent[tiab] OR pre pubescent[tiab] OR prepubescent[tiab] OR kid[tiab] OR kids[tiab] OR early childhood[tiab] OR early years[tiab] OR pre-k[tiab] OR pre-primary[tiab] OR under five*[tiab] OR young child*[tiab] OR head start[tiab] OR prekindergarten[tiab] OR pre-kindergarten[tiab]
  - #4 - (#1 AND #2 AND #3)
  - #5 - (#1 AND #2 AND #3) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2000/01/01 to 2019/07/29; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: July 29, 2019
- Date range searched: January 1, 2000-July 29, 2019
- Search Terms:
  - #1 - [mh “Seafood”] OR [mh “Fishes”] OR [mh “Fish Proteins, Dietary”] OR [mh “Mercury Poisoning”] OR [mh “Ostreidae”] OR [mh “Mya”] OR [mh “Bivalvia”] OR [mh “Pectinidae”] OR [mh “Brachyura”] OR [mh “Decapodiformes”] OR [mh “Fatty Acids, Omega-3”]
  - #2 - (seafood* OR “sea food*” OR “fish consumption” OR fish OR fishes OR “fish products” OR “fatty fish” OR shellfish OR “shellfish protein*” OR “mercury poisoning*” OR methylmercury OR sharks OR swordfish OR tuna OR salmon OR sardines OR pollock OR flounder OR cod OR tilapia OR shrimp OR oysters OR clams OR scallops OR crab OR mackerel OR catfish* OR trout OR lobster OR squid OR halibut OR “mahi mahi” OR crawfish OR anchov* OR herring OR rockfish OR “marine product*”):ti,ab,kw
  - #3 - #1 OR #2
  - #4 - [mh ^“Cardiovascular Diseases”] OR [mh “Heart Failure”] OR [mh “Myocardial Infarction”] OR [mh “Myocardial Ischemia”] OR [mh Stroke] OR [mh “Venous Thrombosis”] OR [mh Lipids/BL] OR [mh “Cholesterol, HDL”] OR [mh “Cholesterol, LDL”] OR [mh “Triglycerides”]
  - #5 - (“cardiovascular disease*” OR “coronary artery disease” OR “heart disease” OR “heart failure” OR “myocardial infarction*” OR “myocardial ischemia*” OR stroke OR angina OR “heart attack” OR “venous thrombosis” OR “hypertension” OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR triglycerides):ti,ab,kw
  - #6 - #4 OR #5
  - #7 - [mh “Child”] OR [mh “Adolescent”]
  - #8 - (child OR children OR youth* OR adolescence OR adolescent* OR teen OR teens OR teenager* OR preteen* OR pre-teen* OR pre-adolesc* OR preadolesc* OR preschool* OR pediatric* OR paediatric* OR boy OR boys OR girl OR girls OR schoolchild* OR “middle school*” OR “high school*” OR juvenile OR pubescent OR “pre pubescent” OR prepubescent OR kid OR kids OR “early childhood” OR “early years” OR pre-k OR pre-primary OR “under five*” OR “young child*” OR “head start” OR prekindergarten OR pre-kindergarten):ti,ab,kw
  - #9 - #7 OR #8
  - #10 - #3 AND #6 AND #9” with Publication Year from 2000 to 2019, in Trials (Word variations have been searched)

#### Embase

- Provider: Elsevier
- Date(s) Searched: July 29, 2019
- Date range searched: January 1, 2000-July 29, 2019
- Search Terms:
  - #1 - ‘sea food’/exp OR ‘fish’/exp OR ‘fish protein’/exp OR ‘mercurialism’/exp OR ‘oyster’/exp OR ‘mya’/de OR ‘bivalve’/exp OR ‘scallop’/exp OR ‘brachyura’/exp OR ‘decapodiformes’/exp OR ‘omega 3 fatty acid’/de
  - #2 - seafood*:ab,ti OR ‘sea food*’:ab,ti OR ‘fish consumption’:ab,ti OR fish:ab,ti OR fishes:ab,ti OR ‘fish products’:ab,ti OR ‘fatty fish’:ab,ti OR shellfish:ab,ti OR ‘shellfish protein*’:ab,ti OR ‘mercury poisoning*’:ab,ti OR methylmercury:ab,ti OR sharks:ab,ti OR swordfish:ab,ti OR tuna:ab,ti OR salmon:ab,ti OR sardines:ab,ti OR pollock:ab,ti OR flounder:ab,ti OR cod:ab,ti OR tilapia:ab,ti OR shrimp:ab,ti OR oysters:ab,ti OR clams:ab,ti OR scallops:ab,ti OR crab:ab,ti OR mackerel:ab,ti OR catfish*:ab,ti OR trout:ab,ti OR lobster:ab,ti OR squid:ab,ti OR halibut:ab,ti OR ‘mahi mahi’:ab,ti OR crawfish:ab,ti OR anchov*:ab,ti OR herring:ab,ti OR rockfish:ab,ti OR ‘marine product*’:ab,ti
  - #3 - #1 OR #2
  - #4 - ‘cardiovascular disease’/exp OR ‘heart failure’/exp OR ‘heart infarction’/exp OR ‘heart muscle ischemia’/exp OR ‘cerebrovascular accident’/exp OR ‘venous thromboembolism’/exp OR ‘lipids in blood’/de OR ‘high density lipoprotein cholesterol’/de OR ‘low density lipoprotein cholesterol’/de OR ‘triacylglycerol’/exp
  - #5 - ‘cardiovascular disease*’:ab,ti OR ‘coronary artery disease’:ab,ti OR ‘heart disease’:ab,ti OR ‘heart failure’:ab,ti OR ‘myocardial infarction*’:ab,ti OR ‘myocardial ischemia*’:ab,ti OR stroke:ab,ti OR angina:ab,ti OR ‘heart attack’:ab,ti OR ‘venous thrombosis’:ab,ti OR ‘hypertension’:ab,ti OR ‘high blood pressure’:ab,ti OR ‘hdl cholesterol’:ab,ti OR ‘ldl cholesterol’:ab,ti OR ‘total cholesterol’:ab,ti OR triglycerides:ab,ti
  - #6 - #4 OR #5
  - #7 - ‘child’/exp OR ‘adolescent’/exp
  - #8 - child:ab,ti OR children:ab,ti OR youth*:ab,ti OR adolescence:ab,ti OR adolescent*:ab,ti OR teen:ab,ti OR teens:ab,ti OR teenager*:ab,ti OR preteen*:ab,ti OR ‘pre teen*’:ab,ti OR ‘pre adolesc*’:ab,ti OR preadolesc*:ab,ti OR preschool*:ab,ti OR pediatric*:ab,ti OR paediatric*:ab,ti OR boy:ab,ti OR boys:ab,ti OR girl:ab,ti OR girls:ab,ti OR schoolchild*:ab,ti OR ‘middle school*’:ab,ti OR ‘high school*’:ab,ti OR juvenile:ab,ti OR pubescent:ab,ti OR ‘pre pubescent’:ab,ti OR prepubescent:ab,ti OR kid:ab,ti OR kids:ab,ti OR ‘early childhood’:ab,ti OR ‘early years’:ab,ti OR ‘pre k’:ab,ti OR ‘pre primary’:ab,ti OR ‘under five*’:ab,ti OR ‘young child*’:ab,ti OR ‘head start’:ab,ti OR prekindergarten:ab,ti OR ‘pre kindergarten’:ab,ti
  - #9 - #7 OR #8
  - #10 - #3 AND #6 AND #9
  - #11 - #3 AND #6 AND #9 AND [humans]/lim AND [english]/lim AND [2000-2019]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

#### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) Searched: July 29, 2019
- Date range searched: January 1, 2000-July 29, 2019
- Search Terms:
  - #S1- (MH “Seafood+”) OR (MH “Fish”) OR (MH “Shellfish”) OR (MH “Mercury Poisoning”) OR (MH “Mollusca”) OR (MH “Fatty Acids, Omega-3+”)
  - #S2 - seafood* OR “sea food*” OR “fish consumption” OR fish OR fishes OR “fish products” OR “fatty fish” OR shellfish OR “shellfish protein*” OR “mercury poisoning*” OR methylmercury OR sharks OR swordfish OR tuna OR salmon OR sardines OR pollock OR flounder OR cod OR tilapia OR shrimp OR oysters OR clams OR scallops OR crab OR mackerel OR catfish* OR trout OR lobster OR squid OR halibut OR “mahi mahi” OR crawfish OR anchov* OR herring OR rockfish OR “marine product*”
  - #S3 - S1 OR S2
  - #S4 - (MH “Cardiovascular Diseases”) OR (MH “Heart Failure+”) OR (MH “Myocardial Infarction+”) OR (MH “Myocardial Ischemia+”) OR (MH “Stroke+”) OR (MH “Venous Thrombosis+”) OR (MH “Lipids/BL”) OR (MH “Lipoproteins, HDL Cholesterol”) OR (MH “Lipoproteins, LDL Cholesterol”) OR (MH “Triglycerides”)
  - #S5 - “cardiovascular disease*” OR “coronary artery disease” OR “heart disease*”OR “heart failure” OR “myocardial infarction*” OR “myocardial Ischemia*” OR stroke OR angina OR “heart attack” OR “venous thrombosis” OR hypertension OR “high blood pressure” OR “HDL cholesterol” OR “LDL cholesterol” OR “total cholesterol” OR triglycerides
  - #S6 - S4 OR S5
  - #S7 - (MH “Child+”) OR (MH “Adolescence+”) OR child OR children OR youth* OR adolescence OR adolescent* OR teen OR teens OR teenager* OR preteen* OR pre-teen* OR pre-adolesc* OR preadolesc* OR preschool* OR pediatric* OR paediatric* OR boy OR boys OR girl OR girls OR schoolchild* OR “middle school*” OR “high school*” OR juvenile OR pubescent OR “pre pubescent” OR prepubescent OR kid OR kids OR “early childhood” OR “early years” OR pre-k OR pre-primary OR “under five*” OR “young child*” OR “head start” OR prekindergarten OR pre-kindergarten
  - #S8 - (S3 AND S6 AND S7) NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication”) Limiters - Publication Year: 2000-2019; Peer Reviewed; English Language; Human

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 5 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between seafood consumption during childhood and adolescence (up to 18 years of age) and risk of cardiovascular disease. The literature search yielded 2,219 articles, with 1,534 articles after duplicates were removed. During title screening, 1,322 articles were screened out. During abstract screening, 152 articles were screened out. During full-text screening, 56 articles were screened out. During the hand search, 0 additional articles were identified to include. A total of 4 articles were included in the systematic review at the end of the search and screening process.

### Excluded articles

The table below (Table 5) lists the articles excluded after full-text screening, and includes columns for the categories of inclusion and exclusion criteria (see Table 4) that studies were excluded based on. At least one reason for exclusion is provided for each article, as indicated by an “X” in one of the columns, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 5 Articles excluded after full-text screening with rationale for exclusion

| Citation | Study Design | Intervention/Exposure | Population at Intervention or Exposure | Outcome | Population at Outcome
1. | Aadland EK, Lavigne C, Graff IE, et al. Lean-seafood intake reduces cardiovascular lipid risk factors in healthy subjects, results from a randomized controlled trial with a crossover design. Am J Clin Nutr. 2015;102(3),582-92. doi:10.3945/ajcn.115.112086. | | | X
2. | Al-Ghannami SS, Sedlak E, Hussein IS, et al. Lipid-soluble nutrient status of healthy Omani school children before and after intervention with oily fish meal or re-esterified triacylglycerol fish oil. Nutrition. 2016;32,73-78. doi:10.1016/j.nut.2015.07.014. | | | | X
3. | Ayer JG, Harmer JA, Xuan W, et al. Dietary supplementation with n-3 polyunsaturated fatty acids in early childhood, effects on blood pressure and arterial structure and function at age 8 y. Am J Clin Nutr. 2009;90(2),438-46. doi:10.3945/ajcn.2009.27811. | | X
4. | Bastida S, Sanchez-Muniz FJ, Cuena R, Perea S, Aragones A. High density lipoprotein-cholesterol changes in children with high cholesterol levels at birth. Eur J Pediatr. 2002;161(2),94-8. doi:10.1007/s00431-001-0863-y. | | X
5. | Bradlee ML, Singer MR, Daniels SR, Moore LL. Eating patterns and lipid levels in older adolescent girls. Nutr Metab Cardiovasc Dis. 2013;23(3),196-204. doi:10.1016/j.numecd.2011.10.010. | | X
6. | Brox J, Bjornstad, E, Olaussen K, Osterud, B, Almdahl S, Lochen ML. Blood lipids fatty acids diet and lifestyle parameters in adolescents from a region in northern Norway with a high mortality from coronary heart disease. Eur J Clin Nutr. 2002;56(7),694-700. doi:10.1038/sj.ejcn.1601381. | | X
7. | Çöl N, Gökçen C, Demırcıoğlu Kiliç, B, Karadağ, M. Prevalence of obesity/hypertension in children and adolescents with ADHD and evaluation of total body composition. Anadolu Psikiyatri Dergisi. 2019;20(1),93-100. | | X | | X
8. | Colussi G, Catena C, Dialti V, Mos L, Sechi LA. Effects of the consumption of fish meals on the carotid IntimaMedia thickness in patients with hypertension, a prospective study. J Atheroscler Thromb. 2014;21(9),941-56. doi:10.5551/jat.22921. | | | X
9. | Couch SC, Crandell J, King I, et al. Associations between long chain polyunsaturated fatty acids and cardiovascular lipid risk factors in youth with type 1 diabetes, SEARCH Nutrition Ancillary Study. J Diabetes Complications. 2017;31(1),67-73. doi:10.1016/j.jdiacomp.2016.10.002. | | X
10. | Cundiff DK, Lanou AJ, Nigg CR. Relation of omega-3 fatty acid intake to other dietary factors known to reduce coronary heart disease risk. Am J Cardiol. 2007;99(9),1230-3. doi:10.1016/j.amjcard.2006.12.032. | | | X | X
11. | Damsgaard CT, Dalskov SM, Laursen RP, et al. Provision of healthy school meals does not affect the metabolic syndrome score in 8-11-year-old children but reduces cardiometabolic risk markers despite increasing waist circumference. Br J Nutr. 2014;112(11),1826-36. doi:10.1017/S0007114514003043. | | X
12. | Dewailly E, Blanchet C, Gingras S, Lemieux S, Holub BJ. Fish consumption and blood lipids in three ethnic groups of Quebec (Canada). Lipids. 2003;38(4),359-65. doi:10.1007/s11745-003-1070-4. doi:10.1007/s11745-003-1070-4. | | | X
13. | Dias CB, Wood LG, Garg ML. Effects of dietary saturated and n-6 polyunsaturated fatty acids on the incorporation of long-chain n-3 polyunsaturated fatty acids into blood lipids. Eur J Clin Nutr. 2016;70(7),812-8. doi:10.1038/ejcn.2015.213. | | X | X
14. | Dorea JG, de Souza JR, Rodrigues P, Ferrari I, Barbosa AC. Hair mercury (signature of fish consumption) and cardiovascular risk in Munduruku and Kayabi Indians of Amazonia. Environ Res. 2005;97(2),209-19. doi:10.1016/j.envres.2004.04.007. | | X | X
15. | Dumont J, Huybrechts I, Spinneker A, et al. FADS1 genetic variability interacts with dietary alpha-linolenic acid intake to affect serum non-HDL-cholesterol concentrations in European adolescents. J Nutr. 2011;141(7),1247-53. doi:10.3945/jn.111.140392. | | X
16. | Fillion M, Mergler D, Sousa Passos CJ, Larribe F, Lemire M, Guimaraes JR. A preliminary study of mercury exposure and blood pressure in the Brazilian Amazon. Environ Health. 2006;5,29. doi:10.1186/1476-069X-5-29. | X | | X
17. | Garneau V, Rudkowska I, Paradis AM, et al. Association between plasma omega-3 fatty acids and cardiovascular disease risk factors. Appl Physiol Nutr Metab. 2013;38(3),243-8. doi:10.1139/apnm-2012-0238. | | | X
18. | Gopinath B, Moshtaghian H, Flood VM, et al. Pattern of omega-3 polyunsaturated fatty acid intake and fish consumption and retinal vascular caliber in children and adolescents, A cohort study. PLoS One. 2017;12(2),e0172109. doi:10.1371/journal.pone.0172109. | | | | X
19. | Guerendiain M, Montes R, López-Belmonte G, et al. Changes in plasma fatty acid composition are associated with improvements in obesity and related metabolic disorders, A therapeutic approach to overweight adolescents. Clin Nutr. 2018;37(1),149-156. doi:10.1016/j.clnu.2016.11.006. | | X
20. | Gump BB, MacKenzie JA, Dumas AK, et al. Fish consumption low-level mercury lipids and inflammatory markers in children. Environ Res. 2012;112,204-11. doi:10.1016/j.envres.2011.10.002. | X
21. | Güneş Ö, Soylu M, İnanç N, et al. Relationship between red blood cell membrane fatty acid composition and dietary fatty acids level in obese adolescents with/without metabolic syndrome. Prog Nutr. 2018;20(4),648-658. doi:10.23751/pn.v20i4.6039. | | X
22. | Haraldsdottir A, Torfadottir JE, Valdimarsdottir UA, et al. Fish and fish-liver oil consumption in adolescence and midlife and risk of CHD in older women. Public Health Nutr. 2016;19(2),318-25. doi: 10.1017/S1368980015001020. | X
23. | Harris CP, von Berg A, Berdel D, et al. Association of dietary fatty acids with blood lipids is modified by physical activity in adolescents, Results from the GINIplus and LISA birth cohort studies. Nutrients. 2018;10(10). doi:10.3390/nu10101372. | X | X
24. | Harris C, Buyken A, Koletzko S, et al. Dietary fatty acids and changes in blood lipids during adolescence, the role of substituting nutrient intakes. Nutrients. 2017;9(2). doi:10.3390/nu9020127. | | X
25. | Hartiala O, Kajander S, Knuuti J, et al. Life-course risk factor levels and coronary artery calcification. The Cardiovascular Risk in Young Finns Study. Int J Cardiol. 2016;225,23-29. doi:10.1016/j.ijcard.2016.09.080. | | | | X
26. | Jaaskelainen P, Magnussen CG, Pahkala K, et al. Childhood nutrition in predicting metabolic syndrome in adults, the cardiovascular risk in Young Finns Study. Diabetes Care. 2012;35(9),1937-43. doi:10.2337/dc12-0019. | | | | X | X
27. | Jang HB, Hwang JY, Park JE,et al. Intake levels of dietary polyunsaturated fatty acids modify the association between the genetic variation in PCSK5 and HDL cholesterol. J Med Genet. 2014;51(12),782-8. doi:10.1136/jmedgenet-2014-102670. | | X
28. | Joki P, Suomalainen H, Jarvinen KM, et al. Cholesterol precursors and plant sterols in children with food allergy. Am J Clin Nutr. 2003;77(1),51-5. doi:10.1093/ajcn/77.1.51. | | X
29. | Julian-Almarcegui C, Vandevijvere S, Gottrand F,et al. Association of heart rate and blood pressure among European adolescents with usual food consumption, The HELENA study. Nutr Metab Cardiovasc Dis. 2016;26(6),541-8. doi:10.1016/j.numecd.2016.01.014. | X
30. | Kaikkonen JE, Jula A, Mikkilä V, et al. Childhood serum cholesterol ester fatty acids are associated with blood pressure 27 y later in the cardiovascular risk in young Finns study. Am J Clin Nutr. 2012;95(6),1422-31. doi:10.3945/ajcn.111.030387. | | X
31. | Katsa ME, Ioannidis A, Zyga S, et al. The effect of nutrition and sleep habits on predisposition for metabolic syndrome in Greek children. J Pediatr Nurs. 2018;40,e2-e8. doi:10.1016/j.pedn.2018.01.012. | X
32. | Kirkhus B, Lamglait A, Eilertsen KE, et al. Effects of similar intakes of marine n-3 fatty acids from enriched food products and fish oil on cardiovascular risk markers in healthy human subjects. Br J Nutr. 2012;107(9),1339-49. doi:10.1017/S0007114511004508. | | | X
33. | Klein-Platat C, Drai J, Oujaa M, Schlienger J, Simon C. Plasma fatty acid composition is associated with the metabolic syndrome and low-grade inflammation in overweight adolescents. Am J Clin Nutr. 2005;82(6),1178-84. doi:10.1093/ajcn/82.6.1178. | | X
34. | Laake I, Pedersen JI, Selmer R, et al. A prospective study of intake of trans-fatty acids from ruminant fat partially hydrogenated vegetable oils and marine oils and mortality from CVD. Br J Nutr. 2012;108(4),743-754. doi:10.1017/S0007114511005897. | | | X
35. | Lauritzen L, Harslof LB, Hellgren LI, Pedersen MH, Molgaard C, Michaelsen KF. Fish intake erythrocyte n-3 fatty acid status and metabolic health in Danish adolescent girls and boys. Br J Nutr. 2012;107(5),697-704. doi:10.1017/S0007114511002418. | X | | | X
36. | Lehtovirta M, Pahkala K, Niinikoski H, et al. Effect of dietary counseling on a comprehensive metabolic profile from childhood to adulthood. J Pediatr. 2018;195,190-198.e3. doi:10.1016/j.jpeds.2017.11.057. | | X
37. | Liu Y, Buchanan S, Anderson HA, Xiao Z, Persky V, Turyk ME. Association of methylmercury intake from seafood consumption and blood mercury level among the Asian and Non-Asian populations in the United States. Environ Res. 2018;160,212-222. doi:10.1016/j.envres.2017.09.031. | | | X | | X
38. | McNaughton SA, Ball K, Mishra GD, Crawford DA. Dietary patterns of adolescents and risk of obesity and hypertension. J Nutr. 2008;138(2),364-70. doi:10.1093/jn/138.2.364. | X
39. | Molven I, Retterstol K, Andersen LF, et al. Children and young adults with familial hypercholesterolaemia (FH) have healthier food choices particularly with respect to dietary fat sources compared with non-FH children. J Nutr Sci. 2013;2,e32. doi:10.1017/jns.2013.27. | X | | | X
40. | Montonen J, Järvinen R, Reunanen A, Knekt P. Fish consumption and the incidence of cerebrovascular disease. Br J Nutr. 2010;102(5),750-6. doi:10.1017/S0007114509274782. | | | X
41. | Nejatinamini S, Ataie-Jafari A, Ghasemian A, et al. Burden of ischemic heart disease attributable to low omega-3 fatty acids intake in Iran, Findings from the global burden of disease study 2010. J Tehran Heart Cent. 2016;11(1),21-29. | | X | X
42. | O’Sullivan TA, Ambrosini GL, Mori TA, Beilin LJ, Oddy WH. Omega-3 Index correlates with healthier food consumption in adolescents and with reduced cardiovascular disease risk factors in adolescent boys. Lipids. 2011;46(1),59-67. doi:10.1007/s11745-010-3499-8. | X | | | X
43. | Pieniak Z, Verbeke W, Perez-Cueto F, Brunso K, De Henauw S. Fish consumption and its motives in households with versus without self-reported medical history of CVD, a consumer survey from five European countries. BMC Public Health. 2008;8,306. doi:10.1186/1471-2458-8-306. | X
44. | Raghuveer G. Assessment of atherosclerotic cardiovascular risk and management of dyslipidemia in obese children. Prog Pediatr Cardiol. 2008;25(2),167-176. doi:10.1016/j.ppedcard.2008.05.005. | X
44. | Rheinberger CM, Hammitt JK. Risk trade-offs in fish consumption, a public health perspective. Environ Sci Technol. 2012;46(22),12337-46. doi:10.1021/es302652m. | X
46. | Sands SA, Reid KJ, Windsor SL, Harris WS. The impact of age body mass index and fish intake on the EPA and DHA content of human erythrocytes. Lipids. 2005;40(4),343-7. doi:10.1007/s11745-006-1392-2 | | | X
47. | Schmedes M, Brejnrod AD, Aadland EK, et al. The effect of lean-seafood and non-seafood diets on fecal metabolites and gut microbiome, results from a randomized crossover intervention study. Mol Nutr Food Res. 2019;63(1),e1700976. doi:10.1002/mnfr.201700976. | | | X
48. | Skilton Michael R. ω-3 Fatty Acids Impaired Fetal Growth and Cardiovascular Risk, Nutrition as Precision Medicine. Adv Nutr. 2018;9(2),99-104. doi:10.1093/advances/nmx012. | X
49. | Strandvik B, Chen Y, Dangardt F, et al. From the Swedish to the Mediterranean diet and the omega-6/omega-3 balance. World Rev Nutr Diet. 2011;102,73-80. doi:10.1159/000327793. | X
50. | Tam CH, Wang Y, Lee HM, et al. Early gene-diet interaction between glucokinase regulatory protein (GCKR) polymorphism vegetable and fish intakes in modulating triglyceride levels in healthy adolescents. Nutr Metab Cardiovasc Dis. 2015;25(10),951-8. doi:10.1016/j.numecd.2015.06.011. | X
51. | Thorsdottir I, Gunnarsdottir I, Palsson GI. Birth weight growth and feeding in infancy, relation to serum lipid concentration in 12-month-old infants. Eur J Clin Nutr. 2003;57(11),1479-85. doi:10.1038/sj.ejcn.1601714. | | X
52. | Thurston SW, Bovet P, Myers GJ, et al. Does prenatal methylmercury exposure from fish consumption affect blood pressure in childhood?. Neurotoxicology. 2007;28(5),924-30. doi:10.1016/j.neuro.2007.06.002. | | X | X
53. | Venalainen TM, Viitasalo AM, Schwab US, et al. Effect of a 2-y dietary and physical activity intervention on plasma fatty acid composition and estimated desaturase and elongase activities in children, the Physical Activity and Nutrition in Children Study. Am J Clin Nutr. 2016;104(4),964-72. doi:10.3945/ajcn.116.136580. | | X
54. | Verduci E, Radaelli G, Salvioni M, Riva E, Giovannini M. Plasma long-chain fatty acids profile and metabolic outcomes in normolipidaemic obese children after one-year nutritional intervention. Acta Paediatr. 2011;100(4),585-9. doi:10.1111/j.1651-2227.2010.02120.x. | | X
55. | Washington RL. Diet may lessen heart disease as SGA infants grow up. J Pediatr. 2015;166(5),1101-4. | X
56. | Zhang W, Zhang X, Tian Y, et al. Risk assessment of total mercury and methylmercury in aquatic products from offshore farms in China. J Hazard Mater. 2018;354,198-205. doi:10.1016/j.jhazmat.2018.04.039. | | X | X

vii Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

viii The Human Development classification was based on the Human Development Index (HDI) ranking (1) from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank (2) was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).